# Report No. 36 Fetal Mortality in the United States: Final 2021–2022 and 2022–Provisional 2023

### Objectives

This report describes changes in total, early, and late fetal mortality between 2022 and 2023 (provisional), as well as fetal mortality by maternal race and Hispanic origin and state of residence. Comparisons are made with findings from 2021 to 2022.

### Methods

Data are based on reports of fetal death filed in the 50 states and the District of Columbia and collected via the National Vital Statistics System. In this report, only fetal deaths reported at 20 weeks of gestation or more are included. Data for 2021 and 2022 are final and data for 2023 are provisional.

### Results

In 2023, the overall fetal mortality rate was 5.52 fetal deaths per 1,000 live births and fetal deaths, which was not significantly different from the 2022 rate (5.48). From 2022 to 2023, the early fetal mortality rate (20–27 weeks of gestation) significantly increased by 4% to 2.89 per 1,000, while the late fetal mortality rate (28 weeks of gestation or more) was essentially unchanged at 2.64. Among the race and Hispanic-origin groups, the fetal mortality rate increased for Asian non-Hispanic women and was not significantly different for other groups. Fetal mortality rates increased in 4 states, declined in 1 state, and were not significantly different for 45 states and the District of Columbia from 2022 to 2023. In comparison, from 2021 to 2022, the fetal mortality rate declined for total, early, and late fetal deaths, as well as for White non-Hispanic women and in five states.

## Introduction

This report presents 2023 provisional national fetal death data for selected maternal and fetal characteristics, providing more timely data for public health surveillance. Changes in fetal mortality rates overall and by maternal race and Hispanic origin and state of residence are examined from 2022 to 2023, and comparisons are made with findings for the period 2021 to 2022.

## Methods

The fetal death data shown in this report were collected via the National Vital Statistics System. Findings are based on data for fetal deaths occurring at 20 weeks of gestation or more to residents of the United States. Fetal death data for 2021 and 2022 are final. Data for 2023 are provisional and are based on reports of fetal death received and processed by the National Center for Health Statistics as of June 13, 2024, representing about 99.7% of the expected count for 2023. Statistics from previous provisional reports have been shown to be consistent with the final statistics for the respective years (1–3).

Fetal mortality rates are computed as the number of fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths at 20 weeks or more. Numbers and rates are also presented for fetal deaths at 20–27 weeks of gestation (early fetal deaths) and 28 weeks of gestation or more (late fetal deaths).

Hispanic origin and race are reported separately on the U.S. Standard Report of Fetal Death. Data shown by Hispanic origin include all people of Hispanic origin of any race. Data for non-Hispanic people are shown separately for each single-race group. Data by race are based on the revised standards issued by the Office of Management and Budget in 1997 (4), which allow for the reporting of a minimum of five race categories either by single race (reported alone) or in combination (more than one race or multiple races). The race and Hispanic-origin groups shown in this report are American Indian and Alaska Native non-Hispanic, single race (subsequently, American Indian and Alaska Native), Asian non-Hispanic, single race (subsequently, Asian), Black non-Hispanic, single race (subsequently, Black), Native Hawaiian and Other Pacific Islander non-Hispanic, single race (subsequently, Native Hawaiian and Other Pacific Islander), White non-Hispanic, single race (subsequently, White), and Hispanic.

Fetal mortality rates by state are based on the mother’s state of residence. The small number of fetal deaths in some states by year can limit the ability to detect statistically significant changes between years and between states.

The difference between rates is statistically significant at the 0.05 level unless otherwise noted. For information on the methods used to test for statistical significance, see the 2022 user guide (5).

## Results

### Changes in total, early, and late fetal mortality rates, 2021–2022 and 2022–2023

- In 2023 (provisional), the total fetal mortality rate was 5.52, which was not significantly different from the rate in 2022 (5.48) (Table 1, Figure 1). From 2021 (5.73) to 2022, the rate declined 4%.
- The early fetal mortality rate (20–27 weeks of gestation) increased by 4% from 2022 (2.79) to 2023 (2.89). From 2021 (2.95) to 2022, the rate declined 5%.
- The late fetal mortality rate (28 weeks of gestation or more) was 2.64 in 2023, which was not significantly different from the rate in 2022 (2.71). From 2021 (2.80) to 2022, the rate declined 3%.

Figure 1 Total, early, and late fetal mortality rates: United States, 2021 and 2022 final and 2023 provisional

^1^Significantly lower than 2021 (p < 0.05).

^2^Significantly higher than 2022 (p < 0.05).

NOTES: Fetal mortality rate is the number of fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths. Early fetal mortality rate is the number of fetal deaths at 20–27 weeks of gestation per 1,000 live births and fetal deaths at 20–27 weeks of gestation. Late fetal mortality rate is the number of fetal deaths at 28 weeks of gestation or more per 1,000 live births and fetal deaths at 28 weeks of gestation or more.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 1 is a bar chart showing the total, early, and late fetal mortality rates for the United States using 2021 and 2022 final and 2023 provisional data.

Table 1 Number of fetal deaths and births and fetal mortality rate, by selected characteristics: United States, final 2021 and 2022 and provisional 2023 data

Selected characteristics | Number of fetal deaths | | | Number of live births | | | Fetal mortality rate^1^ | | | Percent change in rate
Selected characteristics | 2021 | 2022 | 2023 | 2021 | 2022 | 2023 | 2021 | 2022 | 2023 | 2021–2022 | 2022–2023
Total^2^ | 21,105 | 20,202 | 19,943 | 3,664,292 | 3,667,758 | 3,596,017 | 5.73 | 5.48 | 5.52 | †-4 | 1
Early^3^,^4^ | 10,824 | 10,246 | 10,413 | 3,664,292 | 3,667,758 | 3,596,017 | 2.95 | 2.79 | 2.89 | †-5 | †4
Late^4^, ^5^ | 10,281 | 9,956 | 9,530 | 3,664,292 | 3,667,758 | 3,596,017 | 2.80 | 2.71 | 2.64 | †-3 | -3
Non-Hispanic, single race:^6^
American Indian and Alaska Native | 197 | 187 | 167 | 26,124 | 25,721 | 24,571 | 7.48 | 7.22 | 6.75 | -3 | -7
Asian | 846 | 813 | 894 | 213,813 | 218,994 | 215,738 | 3.94 | 3.70 | 4.13 | -6 | †12
Black | 5,173 | 5,194 | 4,910 | 517,889 | 511,439 | 491,494 | 9.89 | 10.05 | 9.89 | 2 | -2
Native Hawaiian and Other Pacific Islander | 95 | 106 | 104 | 9,531 | 10,122 | 10,115 | 9.87 | 10.36 | 10.18 | 5 | -2
White | 9,196 | 8,280 | 8,174 | 1,887,656 | 1,840,739 | 1,787,051 | 4.85 | 4.48 | 4.55 | †-8 | 2
Hispanic^7^ | 4,290 | 4,359 | 4,503 | 885,916 | 937,421 | 945,200 | 4.82 | 4.63 | 4.74 | -4 | 2

† Significant change (p < 0.05).

1 Number of fetal deaths in specified group per 1,000 live births and fetal deaths.

2 Fetal deaths with stated or presumed period of gestation of 20 weeks or more.

3 Fetal deaths at 20‒27 weeks of gestation.

4 Not stated gestational age proportionally distributed.

5 Fetal deaths at 28 weeks of gestation or more.

6 Race and Hispanic origin are reported separately on reports of fetal death; people of Hispanic origin may be of any race. In this table, non-Hispanic women are classified by race. Race categories are consistent with the 1997 Office of Management and Budget standards. Single race is defined as only one race reported on the report of fetal death.

7 Includes all people of Hispanic origin of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

### Changes in fetal mortality rate by race and Hispanic origin, 2021–2022 and 2022–2023

- For Asian women, the fetal mortality rate increased 12% from 2022 (3.70) to 2023 (4.13) (Table 1, Figure 2). The rate for this group was not significantly different between 2021 (3.94) and 2022.
- From 2022 to 2023, the fetal mortality rate did not change significantly for American Indian and Alaska Native (from 7.22 to 6.75), Black (10.05 to 9.89), Native Hawaiian and Other Pacific Islander (10.36 to 10.18), White (4.48 to 4.55), and Hispanic (4.63 to 4.74) women. Rates for these groups were also not significantly different between 2021 and 2022, except for White women, for whom the rate decreased by 8%.

Figure 2 Fetal mortality rate, by race and Hispanic origin of mother: United States, 2021 and 2022 final and 2023 provisional

^1^Significantly higher than 2022 (p < 0.05).

^2^Significantly lower than 2021 (p < 0.05).

^3^People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 2 is a bar chart showing the fetal mortality rate by race and Hispanic origin of mother for the United States using 2021 and 2022 final and 2023 provisional data.

### Change in fetal mortality rate by state, 2021–2022 and 2022–2023

- From 2022 to 2023, the fetal mortality rate increased in four states, ranging from 16% in New Jersey (4.82 to 5.57) to 27% in Colorado (4.87 to 6.19) (Table 2, Figure 3). The rate decreased 13% in Tennessee (6.50 to 5.64). Changes in the rate were not significant for the remaining 45 states and the District of Columbia.
- In contrast, from 2021 to 2022, the fetal mortality rate decreased in 5 states (Alabama, Maryland, New Jersey, Pennsylvania, and Utah) and was not significantly different for 45 states and the District of Columbia.

Figure 3 Changes in fetal mortality rate, by state of residence: United States, 2021–2022 and 2022–provisional 2023

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 3 is two U.S. maps. The first shows the change in fetal mortality rates by state of residence for provisional 2023 compared with final 2022 data. The second shows changes in fetal mortality rates by state of residence for final 2022 compared with final 2021 data.

Table 2 Number of fetal deaths and births and fetal mortality rate, by state of residence: United States, final 2021 and 2022 and provisional 2023 data

Area | Number of fetal deaths | | | Number of live births | | | Fetal mortality rate^1^ | | | Percent change in rate
Area | 2021 | 2022 | 2023 | 2021 | 2022 | 2023 | 2021 | 2022 | 2023 | 2021–2022 | 2022–2023
Alabama | 510 | 426 | 432 | 58,054 | 58,149 | 57,858 | 8.71 | 7.27 | 7.41 | †-17 | 2
Alaska | 57 | 54 | 42 | 9,367 | 9,359 | 9,015 | 6.05 | 5.74 | 4.64 | -5 | -19
Arizona | 485 | 492 | 494 | 77,916 | 78,547 | 78,096 | 6.19 | 6.22 | 6.29 | 0 | 1
Arkansas | 304 | 265 | 248 | 35,965 | 35,471 | 35,264 | 8.38 | 7.42 | 6.98 | -11 | -6
California | 2,243 | 2,115 | 1,996 | 420,608 | 419,104 | 400,108 | 5.30 | 5.02 | 4.96 | -5 | -1
Colorado | 312 | 305 | 383 | 62,949 | 62,383 | 61,494 | 4.93 | 4.87 | 6.19 | -1 | †27
Connecticut | 162 | 175 | 163 | 35,670 | 35,332 | 34,559 | 4.52 | 4.93 | 4.69 | 9 | -5
Delaware | 54 | 56 | 62 | 10,482 | 10,816 | 10,427 | 5.13 | 5.15 | 5.91 | 0 | 15
District of Columbia | 65 | 65 | 53 | 8,660 | 8,075 | 7,896 | 7.45 | 7.99 | 6.67 | 7 | -17
Florida | 1,594 | 1,548 | 1,504 | 216,260 | 224,433 | 221,410 | 7.32 | 6.85 | 6.75 | -6 | -1
Georgia | 1,016 | 1,000 | 960 | 124,073 | 126,130 | 125,120 | 8.12 | 7.87 | 7.61 | -3 | -3
Hawaii | 109 | 97 | 92 | 15,620 | 15,535 | 14,808 | 6.93 | 6.21 | 6.17 | -10 | -1
Idaho | 112 | 91 | 124 | 22,427 | 22,391 | 22,397 | 4.97 | 4.05 | 5.51 | -19 | 36
Illinois | 795 | 737 | 741 | 132,189 | 128,350 | 124,820 | 5.98 | 5.71 | 5.90 | -5 | 3
Indiana | 426 | 439 | 481 | 79,946 | 79,649 | 79,000 | 5.30 | 5.48 | 6.05 | 3 | 10
Iowa | 164 | 163 | 159 | 36,835 | 36,506 | 36,052 | 4.43 | 4.45 | 4.39 | 0 | -1
Kansas | 195 | 205 | 183 | 34,705 | 34,401 | 34,065 | 5.59 | 5.92 | 5.34 | 6 | -10
Kentucky | 329 | 283 | 276 | 52,214 | 52,315 | 51,984 | 6.26 | 5.38 | 5.28 | -14 | -2
Louisiana | 302 | 300 | 284 | 57,437 | 56,479 | 54,927 | 5.23 | 5.28 | 5.14 | 1 | -3
Maine | 67 | 63 | 41 | 12,006 | 12,093 | 11,627 | 5.55 | 5.18 | 3.51 | -7 | -32
Maryland | 457 | 366 | 423 | 68,285 | 68,782 | 65,594 | 6.65 | 5.29 | 6.41 | †-20 | †21
Massachusetts | 290 | 284 | 259 | 69,137 | 68,584 | 67,093 | 4.18 | 4.12 | 3.85 | -1 | -7
Michigan | 601 | 614 | 530 | 104,980 | 102,321 | 99,124 | 5.69 | 5.96 | 5.32 | 5 | -11
Minnesota | 349 | 351 | 321 | 64,425 | 64,015 | 61,715 | 5.39 | 5.45 | 5.17 | 1 | -5
Mississippi | 355 | 320 | 343 | 35,156 | 34,675 | 34,459 | 10.00 | 9.14 | 9.86 | -9 | 8
Missouri | 388 | 358 | 372 | 69,453 | 68,985 | 67,123 | 5.56 | 5.16 | 5.51 | -7 | 7
Montana | 39 | 54 | 49 | 11,231 | 11,175 | 11,078 | 3.46 | 4.81 | 4.40 | 39 | -9
Nebraska | 99 | 110 | 121 | 24,609 | 24,345 | 24,111 | 4.01 | 4.50 | 4.99 | 12 | 11
Nevada | 280 | 235 | 250 | 33,686 | 33,193 | 31,794 | 8.24 | 7.03 | 7.80 | -15 | 11
New Hampshire | 73 | 56 | 44 | 12,625 | 12,077 | 11,936 | 5.75 | 4.62 | 3.67 | -20 | -21
New Jersey | 612 | 498 | 566 | 101,497 | 102,893 | 101,001 | 5.99 | 4.82 | 5.57 | †-20 | †16
New Mexico | 84 | 69 | 96 | 21,391 | 21,614 | 20,951 | 3.91 | 3.18 | 4.56 | -19 | 43
New York (including New York City) | 1,285 | 1,211 | 1,139 | 210,742 | 207,774 | 203,612 | 6.06 | 5.79 | 5.56 | -4 | -4
North Carolina | 652 | 696 | 697 | 120,466 | 121,562 | 120,082 | 5.38 | 5.69 | 5.77 | 6 | 1
North Dakota | 52 | 47 | 42 | 10,112 | 9,567 | 9,647 | 5.12 | 4.89 | 4.33 | -4 | -11
Ohio | 759 | 741 | 777 | 129,791 | 128,231 | 126,896 | 5.81 | 5.75 | 6.09 | -1 | 6
Oklahoma | 269 | 293 | 266 | 48,410 | 48,332 | 47,909 | 5.53 | 6.03 | 5.52 | 9 | -8
Oregon | 187 | 195 | 180 | 40,914 | 39,493 | 38,298 | 4.55 | 4.91 | 4.68 | 8 | -5
Pennsylvania | 777 | 663 | 592 | 132,622 | 130,252 | 126,951 | 5.82 | 5.06 | 4.64 | †-13 | -8
Rhode Island | 56 | 52 | 49 | 10,464 | 10,269 | 9,805 | 5.32 | 5.04 | 4.97 | -5 | -1
South Carolina | 323 | 288 | 310 | 57,185 | 57,820 | 57,729 | 5.62 | 4.96 | 5.34 | -12 | 8
South Dakota | 76 | 54 | 84 | 11,369 | 11,201 | 11,201 | 6.64 | 4.80 | 7.44 | -28 | 55
Tennessee | 537 | 538 | 471 | 81,717 | 82,265 | 83,021 | 6.53 | 6.50 | 5.64 | 0 | †-13
Texas | 1,457 | 1,613 | 1,593 | 373,594 | 389,741 | 387,945 | 3.88 | 4.12 | 4.09 | 6 | -1
Utah | 309 | 252 | 296 | 46,712 | 45,768 | 45,019 | 6.57 | 5.48 | 6.53 | †-17 | †19
Vermont | 27 | 21 | 19 | 5,384 | 5,316 | 5,065 | 4.99 | 3.93 | 3.74 | -21 | -5
Virginia | 493 | 497 | 496 | 95,825 | 95,630 | 92,649 | 5.12 | 5.17 | 5.33 | 1 | 3
Washington | 451 | 421 | 430 | 83,911 | 83,333 | 80,932 | 5.35 | 5.03 | 5.29 | -6 | 5
West Virginia | 93 | 70 | 62 | 17,198 | 16,929 | 16,606 | 5.38 | 4.12 | 3.72 | -23 | -10
Wisconsin | 321 | 320 | 315 | 61,781 | 60,049 | 59,754 | 5.17 | 5.30 | 5.24 | 3 | -1
Wyoming | 53 | 36 | 33 | 6,237 | 6,049 | 5,990 | 8.43 | 5.92 | 5.48 | -30 | -7

† Significant change (p < 0.05).

1 Number of fetal deaths per 1,000 live births and fetal deaths.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

## Summary

This analysis of provisional 2023 fetal mortality data found that the overall fetal mortality rate was not significantly different from the 2022 rate; however, the early fetal mortality rate increased by 4%. The late fetal mortality rate was essentially unchanged. During this time, the rate increased by 12% for Asian women, while no significant change was observed in the rate for all other race and Hispanic-origin groups. Fetal mortality rates increased in four states and declined in one state from 2022 to 2023; however, the small number of fetal deaths in some states by year can limit the ability to detect statistically significant changes between years and between states.

In comparison, between 2021 and 2022, the fetal mortality rate declined for total, early, and late fetal deaths, as well as for White women. Rates also declined for five states.

## References

1 Gregory ECW, Valenzuela CP, Martin JA. Fetal mortality in the United States: Trends from 2014 through 2019 and changes between 2018–2019 and 2019–2020. Vital Statistics Rapid Release; no 18. Hyattsville, MD: National Center for Health Statistics. 2022. DOI: 10.15620/cdc:113008.
2 Gregory ECW, Valenzuela CP, Martin JA. Fetal mortality in the United States: Final 2019–2020 and 2020–provisional 2021. Vital Statistics Rapid Release; no 26. Hyattsville, MD: National Center for Health Statistics. 2023. DOI: 10.15620/cdc:122292.
3 Gregory ECW, Valenzuela CP, Martin JA. Fetal mortality in the United States: Final 2020–2021 and 2021–provisional 2022. Vital Statistics Rapid Release; no 32. Hyattsville, MD: National Center for Health Statistics. 2023. DOI: 10.15620/cdc:133319.
4 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist 62(210):58782–90. 1997.
5 National Center for Health Statistics. User guide to the 2022 fetal death public use file. 2024. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/fetaldeath/2022fetaluserguide.pdf.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Acting Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science