# Volume 75, Number 7 Deaths: Leading Causes for 2024

### Objectives

This report presents final 2024 data on the 10 leading causes of death in the United States by age group, race and Hispanic origin, and sex. Leading causes of infant, neonatal, and postneonatal death are also presented. This report supplements “Deaths: Final Data for 2024,” the National Center for Health Statistics’ annual report of final mortality statistics.

### Methods

Data in this report are based on information from all death certificates filed in the 50 states and the District of Columbia in 2024. Causes of death classified by the International Classification of Diseases, 10th Revision are ranked according to the number of deaths. Cause-of-death statistics are based on the underlying cause of death.

### Results

In 2024, the ranked order of 9 of the 10 leading causes of death remained unchanged from 2023. The 10 leading causes of death in 2024 in ranked order were: Diseases of heart; Malignant neoplasms; Accidents (unintentional injuries); Cerebrovascular diseases; Chronic lower respiratory diseases; Alzheimer disease; Diabetes mellitus; Nephritis, nephrotic syndrome and nephrosis; Chronic liver disease and cirrhosis; and Intentional self-harm (suicide). These causes accounted for 70.9% of all deaths occurring in the United States. Rankings are presented by age, race, Hispanic origin, and sex. The 10 leading causes of infant death for 2024 in ranked order were: Congenital malformations, deformations and chromosomal abnormalities; Disorders related to short gestation and low birth weight, not elsewhere classified; Sudden infant death syndrome; Accidents (unintentional injuries); Newborn affected by maternal complications of pregnancy; Bacterial sepsis of newborn; Newborn affected by complications of placenta, cord and membranes; Respiratory distress of newborn; Diseases of the circulatory system; and Intrauterine hypoxia and birth asphyxia.

## Introduction

Ranking causes of death is a standard and widely used method of presenting mortality statistics. Leading cause-of-death data have been published since 1952 (beginning with 1949 mortality data), when official tabulations ranking causes of death were first introduced (1). Users of this method of presentation should be aware of its limitations. Ranking causes of death is, to some extent, a subjective procedure. The ranked order of any particular cause of death will depend on the list of causes from which the selection is made and on the rules applied in making the selection. Different cause lists and ranking rules will typically produce different leading causes of death. Recognizing the need for a consistent ranking procedure for use by state health departments and the National Office of Vital Statistics, in 1951 the Public Health Conference on Records and Statistics recommended that state and federal agencies responsible for identifying diseases of public health importance adopt a uniform ranking procedure using a standard list of causes of death (2). The procedures implemented in 1952 are essentially the same as those currently used by the National Center for Health Statistics (NCHS); however, the cause-of-death lists have been expanded and altered over time with each subsequent revision of the International Classification of Diseases (ICD). Cause-of-death data are based on the underlying cause of death.

Cause-of-death ranking is useful for showing the relative burden of cause-specific mortality. However, it should be used with a clear understanding of what the rankings mean. Literally, the rankings signify the most frequently occurring causes of death among those causes eligible to be ranked. Rankings do not illustrate cause-specific mortality risk as depicted by mortality rates. The rank of a specific cause (as in its mortality burden relative to other causes) may decline over time even if its mortality rate has not changed, or its rank may remain the same over time even if its mortality rate is declining.

Rankings also do not necessarily indicate the causes of death of greatest public health importance. Some causes of death of public health significance are excluded from the ranking procedure. For example, Malignant neoplasms of the trachea, bronchus and lung (lung cancer) and Motor vehicle accidents are not rankable causes of death (see “Procedures for ranking causes of death”), although they can be identified using the standard mortality tabulation lists. If these causes were included in the current rankings, lung cancer would be placed among the 10 leading causes of death with a rank of 6th, whereas Motor vehicle accidents would rank 13th. However, each of these is incorporated into broader rankable categories, namely, Malignant neoplasms (cancer) and Accidents (unintentional injuries), respectively. Although not perfectly suitable in all circumstances, the current framework provides a rankable list of causes of death that has broad appeal and acceptance in the public health community.

This report also uses the percentage of total deaths from the rankable causes to show the relative burden of cause-specific mortality. This maps directly to the rankings such that, within a given year or population group, the causes with the highest rankings also have the highest proportion of total deaths. When making comparisons over time, however, note that the rank of a specific cause may remain the same even though the percentage of deaths attributable to that cause may have changed. Similarly, two population groups may have the same rank for a specific cause but different attributable percentages.

This report presents final 2024 data on leading causes of death in the United States by age group, race and Hispanic origin, and sex. It shows race and Hispanic-origin categories based on the 1997 Office of Management and Budget (OMB) standards for collecting, tabulating, and reporting race and Hispanic ethnicity (3). For details on the differences between the 1997 OMB standards and the previous 1977 standards, see “Comparability of Race-specific Mortality Data Based on 1977 Versus 1997 Reporting Standards” (4). This report supplements “Deaths: Final Data for 2024,” which separately presents final national mortality statistics for 2024 (5). Also presented in this report is the procedure used by NCHS to rank causes of death, along with tables showing causes that are designated as “rankable.”

## Data and Methods

### Data

Data in this report are based on information from all death certificates filed in the 50 states and the District of Columbia (D.C.) in 2024. Death certificates are generally completed by funeral directors, attending physicians, medical examiners, and coroners. Cause-of-death statistics for 2024 presented in this report are classified according to the 10th Revision of ICD (ICD–10) (6). Discussions of the cause-of-death classification and coding rule changes in data year 2024 are provided in the Technical Notes at the end of this report.

### Procedures for ranking causes of death

The procedures that NCHS uses for ranking causes of death are consistent with the recommendations of the 1951 Public Health Conference on Records and Statistics (2). Causes are ranked according to the number of deaths assigned to rankable causes. The number of deaths is used as the ranking criterion because it most accurately reflects the frequency of cause-specific mortality.

Although crude death rates could technically be used as the ranking criterion because the population denominator of each rate is constant across all cause-of-death categories, these rates are not ideal. Crude death rates are typically expressed per 100,000 population and are often rounded to one decimal place, reducing the precision of the ranking criterion. This is especially problematic when ranking causes of death for small population subgroups or geographic areas because it may be impossible to differentiate the ranks for several causes. Age-adjusted death rates should never be used to rank causes of death. The numerical value of the age-adjusted death rate depends on the population age distribution used to standardize the rate (7). Consequently, rankings based on age-adjusted death rates will tend to vary depending on which standard is used. For example, when the standard age distribution gives more weight to the older population, the rank of causes of death that primarily affect the older population tends to be higher, and the rank of causes that primarily affect the younger population tends to be lower.

The original cause list from which rankable causes of death were selected according to the recommendations of the 1951 conference (2) was the “List of 64 Selected Causes of Death,” prepared for use with the sixth revision of ICD. With each subsequent ICD revision, the cause list from which rankable causes are selected has changed to reflect the improved classification system. Developed for use with ICD–10, the “List of 113 Selected Causes of Death and Enterocolitis due to Clostridium difficile and COVID-19” (8), shown in Table A, is used to select 52 rankable causes (denoted by #) from which the leading causes presented in Table 1 are derived. Enterocolitis due to Clostridium difficile was added to the list of rankable causes in data year 2006 because of a substantial increase in the number of deaths due to this cause from 1999 through 2006 (9,10). COVID-19 was added in data year 2020 due to its emergence as a leading cause of death.

Table A List of 113 selected causes of death and Enterocolitis due to Clostridium difficile and COVID-19

[An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10)]

Number^†^ | Cause of death (based on ICD–10)
1# | Salmonella infections(A01–A02)
2# | Shigellosis and amebiasis(A03,A06)
3 | Certain other intestinal infections(A04,A07–A09)
# | Tuberculosis(A16–A19)
4 | Respiratory tuberculosis(A16)
5 | Other tuberculosis(A17–A19)
6# | Whooping cough(A37)
7# | Scarlet fever and erysipelas(A38,A46)
8# | Meningococcal infection(A39)
9# | Septicemia(A40–A41)
10# | Syphilis(A50–A53)
11# | Acute poliomyelitis(A80)
12# | Arthropod–borne viral encephalitis(A83–A84,A85.2)
13# | Measles(B05)
14# | Viral hepatitis(B15–B19)
15# | Human immunodeficiency virus (HIV) disease(B20–B24)
16# | Malaria(B50–B54)
17 | Other and unspecified infectious and parasitic diseases and their sequelae(A00,A05,A20–A36,A42–A44,A48–A49,A54–A79,A81–A82,A85.0–A85.1,A85.8,A86–B04,B06–B09,B25–B49,B55–B99)
# | Malignant neoplasms(C00–C97)
18 | Malignant neoplasms of lip, oral cavity and pharynx(C00–C14)
19 | Malignant neoplasm of esophagus(C15)
20 | Malignant neoplasm of stomach(C16)
21 | Malignant neoplasms of colon, rectum and anus(C18–C21)
22 | Malignant neoplasms of liver and intrahepatic bile ducts(C22)
23 | Malignant neoplasm of pancreas(C25)
24 | Malignant neoplasm of larynx(C32)
25 | Malignant neoplasms of trachea, bronchus and lung(C33–C34)
26 | Malignant melanoma of skin(C43)
27 | Malignant neoplasm of breast(C50)
28 | Malignant neoplasm of cervix uteri(C53)
29 | Malignant neoplasms of corpus uteri and uterus, part unspecified(C54–C55)
30 | Malignant neoplasm of ovary(C56)
31 | Malignant neoplasm of prostate(C61)
32 | Malignant neoplasms of kidney and renal pelvis(C64–C65)
33 | Malignant neoplasm of bladder(C67)
34 | Malignant neoplasms of meninges, brain and other parts of central nervous system(C70–C72)
| Malignant neoplasms of lymphoid, hematopoietic and related tissue(C81–C96)
35 | Hodgkin disease(C81)
36 | Non-Hodgkin lymphoma(C82–C85)
37 | Leukemia(C91–C95)
38 | Multiple myeloma and immunoproliferative neoplasms(C88,C90)
39 | Other and unspecified malignant neoplasms of lymphoid, hematopoietic and related tissue(C96)
40 | All other and unspecified malignant neoplasms(C17,C23–C24,C26–C31,C37–C41,C44–C49,C51–C52,C57–C60,C62–C63,C66,C68–C69,C73–C80,C97)
41# | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48)
42# | Anemias(D50–D64)
43# | Diabetes mellitus(E10–E14)
# | Nutritional deficiencies(E40–E64)
44 | Malnutrition(E40–E46)
45 | Other nutritional deficiencies(E50–E64)
46# | Meningitis(G00,G03)
47# | Parkinson disease(G20–G21)
48# | Alzheimer disease(G30)
| Major cardiovascular diseases(I00–I78)
# | Diseases of heart(I00–I09,I11,I13,I20–I51)
49 | Acute rheumatic fever and chronic rheumatic heart diseases(I00–I09)
50 | Hypertensive heart disease(I11)
51 | Hypertensive heart and renal disease(I13)
| Ischemic heart diseases(I20–I25)
52 | Acute myocardial infarction(I21–I22)
53 | Other acute ischemic heart diseases(I24)
| Other forms of chronic ischemic heart disease(I20,I25)
54 | Atherosclerotic cardiovascular disease, so described(I25.0)
55 | All other forms of chronic ischemic heart disease(I20,I25.1–I25.9)
| Other heart diseases(I26–I51)
56 | Acute and subacute endocarditis(I33)
57 | Diseases of pericardium and acute myocarditis(I30–I31,I40)
58 | Heart failure(I50)
59 | All other forms of heart disease(I26–I28,I34–I38,I42–I49,I51)
60# | Essential hypertension and hypertensive renal disease(I10,I12,I15)
61# | Cerebrovascular diseases(I60–I69)
62# | Atherosclerosis(I70)
| Other diseases of circulatory system(I71–I78)
63# | Aortic aneurysm and dissection(I71)
64 | Other diseases of arteries, arterioles and capillaries(I72–I78)
65 | Other disorders of circulatory system(I80–I99)
# | Influenza and pneumonia(J09–J18)
66 | Influenza(J09–J11)
67 | Pneumonia(J12–J18)
| Other acute lower respiratory infections(J20–J22,U04)
68# | Acute bronchitis and bronchiolitis(J20–J21)
69 | Other and unspecified acute lower respiratory infection(J22,U04)
# | Chronic lower respiratory diseases(J40–J47)
70 | Bronchitis, chronic and unspecified(J40–J42)
71 | Emphysema(J43)
72 | Asthma(J45–J46)
73 | Other chronic lower respiratory diseases(J44,J47)
74# | Pneumoconioses and chemical effects(J60–J66,J68,U07.0)
75# | Pneumonitis due to solids and liquids(J69)
76 | Other diseases of respiratory system(J00–J06,J30–J39,J67,J70–J98)
77# | Peptic ulcer(K25–K28)
78# | Diseases of appendix(K35–K38)
79# | Hernia(K40–K46)
# | Chronic liver disease and cirrhosis(K70,K73–K74)
80 | Alcoholic liver disease(K70)
81 | Other chronic liver disease and cirrhosis(K73–K74)
82# | Cholelithiasis and other disorders of gallbladder(K80–K82)
# | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27)
83 | Acute and rapidly progressive nephritic and nephrotic syndrome(N00–N01,N04)
84 | Chronic glomerulonephritis, nephritis and nephropathy not specified as acute or chronic, and renal sclerosis unspecified(N02–N03,N05–N07,N26)
85 | Renal failure(N17–N19)
86 | Other disorders of kidney(N25,N27)
87# | Infections of kidney(N10–N12,N13.6,N15.1)
88# | Hyperplasia of prostate(N40)
89# | Inflammatory diseases of female pelvic organs(N70–N76)
# | Pregnancy, childbirth and the puerperium(O00–O99)
90 | Pregnancy with abortive outcome(O00–O07)
91 | Other complications of pregnancy, childbirth and the puerperium(O10–O99)
92# | Certain conditions originating in the perinatal period(P00–P96)
93# | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99)
94 | Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified(R00–R99)
95 | All other diseases(residual)
# | Accidents (unintentional injuries)(V01–X59,Y85–Y86)
| Transport accidents(V01–V99,Y85)
96 | Motor vehicle accidents(V02–V04,V09.0,V09.2,V12–V14,V19.0–V19.2,V19.4–V19.6,V20–V79,V80.3–V80.5,V81.0–V81.1,V82.0–V82.1,V83–V86,V87.0–V87.8,V88.0–V88.8,V89.0,V89.2)
97 | Other land transport accidents(V01,V05–V06,V09.1,V09.3–V09.9,V10–V11,V15–V18,V19.3,V19.8–V19.9,V80.0–V80.2,V80.6–V80.9,V81.2–V81.9,V82.2–V82.9,V87.9,V88.9,V89.1,V89.3,V89.9)
98 | Water, air and space, and other and unspecified transport accidents and their sequelae(V90–V99,Y85)
| Nontransport accidents(W00–X59,Y86)
99 | Falls(W00–W19)
100 | Accidental discharge of firearms(W32–W34)
101 | Accidental drowning and submersion(W65–W74)
102 | Accidental exposure to smoke, fire and flames(X00–X09)
103 | Accidental poisoning and exposure to noxious substances(X40–X49)
104 | Other and unspecified nontransport accidents and their sequelae(W20–W31,W35–W64,W75–W99,X10–X39,X50–X59,Y86)
# | Intentional self–harm (suicide)(*U03,X60–X84,Y87.0)
105 | Intentional self–harm (suicide) by discharge of firearms(X72–X74)
106 | Intentional self–harmAIOS(suicide) by other and unspecified means and their sequelae(*U03,X60–X71,X75–X84,Y87.0)
# | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1)
107 | Assault (homicide) by discharge of firearms(*U01.4,X93–X95)
108 | Assault (homicide) by other and unspecified means and their sequelae(*U01.0–*U01.3,*U01.5–*U01.9,*U02,X85–X92,X96–Y09,Y87.1)
109# | Legal intervention(Y35,Y89.0)
| Events of undetermined intent(Y10–Y34,Y87.2,Y89.9)
110 | Discharge of firearms, undetermined intent(Y22–Y24)
111 | Other and unspecified events of undetermined intent and their sequelae(Y10–Y21,Y25–Y34,Y87.2,Y89.9)
112# | Operations of war and their sequelae(Y36,Y89.1)
113# | Complications of medical and surgical care(Y40–Y84,Y88)
# | Enterocolitis due to Clostridium difficile(A04.7)^§^
# | COVID-19(U07.1)

†Causes labeled # are ranked to determine leading causes of death for specified population groups. Only mutually exclusive categories are numbered.

§Included in "Certain other intestinal infections (A04,A07–A09)" shown above.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 1 Deaths, percentage of total deaths, and death rate for the 10 leading causes of death in selected age groups, by race and Hispanic origin and sex: United States, 2024

[Rates are per 100,000 population in specified group. Race and Hispanic-origin categories are consistent with 1997 Office of Management and Budget standards. Race and Hispanic origin are reported separately on the death certificate. People of Hispanic origin may be of any race. Data for Hispanic people are not tabulated by race; data for non-Hispanic people are tabulated by race. Data for racial and ethnic groups other than Black non-Hispanic and White non-Hispanic should be interpreted with caution because of misreporting of Hispanic origin and race on the death certificate. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10)]

Rank^†^ | Cause of death (based on ICD–10), race and Hispanic origin, sex, and age group | Number^§,¶^ | Percent of total deaths** | Death rate^§,¶^
| All races, all origins, both sexes, all ages^††^
… | All causes | 3,072,666 | 100.0 | 903.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 683,491 | 22.2 | 201.0
2 | Malignant neoplasms(C00–C97) | 619,876 | 20.2 | 182.3
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 197,449 | 6.4 | 58.1
4 | Cerebrovascular diseases(I60–I69) | 166,852 | 5.4 | 49.1
5 | Chronic lower respiratory diseases(J40–J47) | 145,643 | 4.7 | 42.8
6 | Alzheimer disease(G30) | 116,022 | 3.8 | 34.1
7 | Diabetes mellitus(E10–E14) | 94,445 | 3.1 | 27.8
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 55,081 | 1.8 | 16.2
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | 52,274 | 1.7 | 15.4
10 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 48,824 | 1.6 | 14.4
… | All other causes(residual) | 892,709 | 29.1 | 262.5
| All races, all origins, both sexes, 1–4
… | All causes | 3,843 | 100.0 | 25.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,252 | 32.6 | 8.4
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 402 | 10.5 | 2.7
3 | Malignant neoplasms(C00–C97) | 278 | 7.2 | 1.9
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 268 | 7.0 | 1.8
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 134 | 3.5 | 0.9
6 | Influenza and pneumonia(J09–J18) | 121 | 3.1 | 0.8
7 | Cerebrovascular diseases(I60–I69) | 62 | 1.6 | 0.4
7 | Septicemia(A40–A41) | 62 | 1.6 | 0.4
9 | Certain conditions originating in the perinatal period(P00–P96) | 60 | 1.6 | 0.4
10 | COVID-19(*U07.1) | 38 | 1.0 | 0.3
… | All other causes(residual) | 1,166 | 30.3 | 7.8
| All races, all origins, both sexes, 5–9
… | All causes | 2,532 | 100.0 | 12.5
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 719 | 28.4 | 3.6
2 | Malignant neoplasms(C00–C97) | 400 | 15.8 | 2.0
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 225 | 8.9 | 1.1
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 146 | 5.8 | 0.7
5 | Influenza and pneumonia(J09–J18) | 91 | 3.6 | 0.5
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 80 | 3.2 | 0.4
7 | Chronic lower respiratory diseases(J40–J47) | 57 | 2.3 | 0.3
8 | Cerebrovascular diseases(I60–I69) | 49 | 1.9 | 0.2
9 | Septicemia(A40–A41) | 36 | 1.4 | 0.2
10 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 25 | 1.0 | 0.1
… | All other causes(residual) | 704 | 27.8 | 3.5
| All races, all origins, both sexes, 10–14
… | All causes | 3,408 | 100.0 | 16.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 795 | 23.3 | 3.8
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 487 | 14.3 | 2.3
3 | Malignant neoplasms(C00–C97) | 446 | 13.1 | 2.1
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 290 | 8.5 | 1.4
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 203 | 6.0 | 1.0
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 100 | 2.9 | 0.5
7 | Chronic lower respiratory diseases(J40–J47) | 79 | 2.3 | 0.4
8 | Influenza and pneumonia(J09–J18) | 69 | 2.0 | 0.3
9 | Cerebrovascular diseases(I60–I69) | 59 | 1.7 | 0.3
10 | Septicemia(A40–A41) | 37 | 1.1 | 0.2
… | All other causes(residual) | 843 | 24.7 | 4.0
| All races, all origins, both sexes, 15–19
… | All causes | 11,406 | 100.0 | 51.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,235 | 37.1 | 18.9
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 2,148 | 18.8 | 9.6
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 2,106 | 18.5 | 9.4
4 | Malignant neoplasms(C00–C97) | 633 | 5.5 | 2.8
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 299 | 2.6 | 1.3
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 232 | 2.0 | 1.0
7 | Chronic lower respiratory diseases(J40–J47) | 82 | 0.7 | 0.4
8 | Diabetes mellitus(E10–E14) | 75 | 0.7 | 0.3
9 | Influenza and pneumonia(J09–J18) | 74 | 0.6 | 0.3
10 | Legal intervention(Y35,Y89.0) | 65 | 0.6 | 0.3
… | All other causes(residual) | 1,457 | 12.8 | 6.5
| All races, all origins, both sexes, 20–24
… | All causes | 18,547 | 100.0 | 82.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 7,470 | 40.3 | 33.3
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 3,809 | 20.5 | 17.0
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 2,611 | 14.1 | 11.6
4 | Malignant neoplasms(C00–C97) | 788 | 4.2 | 3.5
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 532 | 2.9 | 2.4
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 241 | 1.3 | 1.1
7 | Diabetes mellitus(E10–E14) | 175 | 0.9 | 0.8
8 | Chronic lower respiratory diseases(J40–J47) | 126 | 0.7 | 0.6
9 | Pregnancy, childbirth and the puerperium(O00–O99) | 125 | 0.7 | 0.6
10 | Cerebrovascular diseases(I60–I69) | 106 | 0.6 | 0.5
… | All other causes(residual) | 2,564 | 13.8 | 11.4
| All races, all origins, both sexes, 25–34
… | All causes | 57,827 | 100.0 | 124.5
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 23,019 | 39.8 | 49.6
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 7,993 | 13.8 | 17.2
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 4,877 | 8.4 | 10.5
4 | Malignant neoplasms(C00–C97) | 3,659 | 6.3 | 7.9
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 3,511 | 6.1 | 7.6
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,591 | 2.8 | 3.4
7 | Diabetes mellitus(E10–E14) | 1,051 | 1.8 | 2.3
8 | Cerebrovascular diseases(I60–I69) | 535 | 0.9 | 1.2
9 | Influenza and pneumonia(J09–J18) | 493 | 0.9 | 1.1
10 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 475 | 0.8 | 1.0
… | All other causes(residual) | 10,623 | 18.4 | 22.9
| All races, all origins, both sexes, 35–44
… | All causes | 97,430 | 100.0 | 213.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 29,138 | 29.9 | 64.0
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 11,607 | 11.9 | 25.5
3 | Malignant neoplasms(C00–C97) | 11,583 | 11.9 | 25.4
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 8,514 | 8.7 | 18.7
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 5,008 | 5.1 | 11.0
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 4,137 | 4.2 | 9.1
7 | Diabetes mellitus(E10–E14) | 2,585 | 2.7 | 5.7
8 | Cerebrovascular diseases(I60–I69) | 2,086 | 2.1 | 4.6
9 | Influenza and pneumonia(J09–J18) | 1,026 | 1.1 | 2.3
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 887 | 0.9 | 1.9
… | All other causes(residual) | 20,859 | 21.4 | 45.8
| All races, all origins, both sexes, 45–54
… | All causes | 157,770 | 100.0 | 386.9
1 | Malignant neoplasms(C00–C97) | 32,451 | 20.6 | 79.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 29,624 | 18.8 | 72.6
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 25,241 | 16.0 | 61.9
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 8,314 | 5.3 | 20.4
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 7,677 | 4.9 | 18.8
6 | Diabetes mellitus(E10–E14) | 6,543 | 4.1 | 16.0
7 | Cerebrovascular diseases(I60–I69) | 5,192 | 3.3 | 12.7
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 2,524 | 1.6 | 6.2
9 | Chronic lower respiratory diseases(J40–J47) | 2,470 | 1.6 | 6.1
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 2,337 | 1.5 | 5.7
… | All other causes(residual) | 35,397 | 22.4 | 86.8
| All races, all origins, both sexes, 55–64
… | All causes | 358,196 | 100.0 | 859.8
1 | Malignant neoplasms(C00–C97) | 98,592 | 27.5 | 236.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 76,501 | 21.4 | 183.6
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 28,628 | 8.0 | 68.7
4 | Diabetes mellitus(E10–E14) | 15,581 | 4.3 | 37.4
5 | Chronic lower respiratory diseases(J40–J47) | 15,113 | 4.2 | 36.3
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 14,261 | 4.0 | 34.2
7 | Cerebrovascular diseases(I60–I69) | 13,222 | 3.7 | 31.7
8 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 7,749 | 2.2 | 18.6
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 5,838 | 1.6 | 14.0
10 | Septicemia(A40–A41) | 5,374 | 1.5 | 12.9
… | All other causes(residual) | 77,337 | 21.6 | 185.6
| All races, all origins, both sexes, 65 and older
… | All causes | 2,341,600 | 100.0 | 3,827.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 560,828 | 24.0 | 916.7
2 | Malignant neoplasms(C00–C97) | 470,997 | 20.1 | 769.9
3 | Cerebrovascular diseases(I60–I69) | 145,402 | 6.2 | 237.7
4 | Chronic lower respiratory diseases(J40–J47) | 126,630 | 5.4 | 207.0
5 | Alzheimer disease(G30) | 114,509 | 4.9 | 187.2
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 75,699 | 3.2 | 123.7
7 | Diabetes mellitus(E10–E14) | 68,387 | 2.9 | 111.8
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 45,583 | 1.9 | 74.5
9 | Parkinson disease(G20–G21) | 39,935 | 1.7 | 65.3
10 | Influenza and pneumonia(J09–J18) | 39,204 | 1.7 | 64.1
… | All other causes(residual) | 654,426 | 27.9 | 1,069.7
| All races, all origins, both sexes, 65–74
… | All causes | 628,416 | 100.0 | 1,772.9
1 | Malignant neoplasms(C00–C97) | 181,340 | 28.9 | 511.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 136,135 | 21.7 | 384.1
3 | Chronic lower respiratory diseases(J40–J47) | 38,935 | 6.2 | 109.8
4 | Cerebrovascular diseases(I60–I69) | 28,143 | 4.5 | 79.4
5 | Diabetes mellitus(E10–E14) | 24,780 | 3.9 | 69.9
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 23,515 | 3.7 | 66.3
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 13,564 | 2.2 | 38.3
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 12,034 | 1.9 | 34.0
9 | Septicemia(A40–A41) | 9,925 | 1.6 | 28.0
10 | Influenza and pneumonia(J09–J18) | 9,478 | 1.5 | 26.7
… | All other causes(residual) | 150,567 | 24.0 | 424.8
| All races, all origins, both sexes, 75–84
… | All causes | 822,944 | 100.0 | 4,264.0
1 | Malignant neoplasms(C00–C97) | 183,662 | 22.3 | 951.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 181,701 | 22.1 | 941.5
3 | Chronic lower respiratory diseases(J40–J47) | 51,013 | 6.2 | 264.3
4 | Cerebrovascular diseases(I60–I69) | 48,926 | 5.9 | 253.5
5 | Alzheimer disease(G30) | 37,364 | 4.5 | 193.6
6 | Diabetes mellitus(E10–E14) | 25,936 | 3.2 | 134.4
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 24,188 | 2.9 | 125.3
8 | Parkinson disease(G20–G21) | 18,764 | 2.3 | 97.2
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 17,055 | 2.1 | 88.4
10 | Influenza and pneumonia(J09–J18) | 13,547 | 1.6 | 70.2
… | All other causes(residual) | 220,788 | 26.8 | 1,144.0
| All races, all origins, both sexes, 85 and older
… | All causes | 890,240 | 100.0 | 13,834.0
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 242,992 | 27.3 | 3,776.0
2 | Malignant neoplasms(C00–C97) | 105,995 | 11.9 | 1,647.1
3 | Cerebrovascular diseases(I60–I69) | 68,333 | 7.7 | 1,061.9
4 | Alzheimer disease(G30) | 67,807 | 7.6 | 1,053.7
5 | Chronic lower respiratory diseases(J40–J47) | 36,682 | 4.1 | 570.0
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 27,996 | 3.1 | 435.0
7 | Diabetes mellitus(E10–E14) | 17,671 | 2.0 | 274.6
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 16,494 | 1.9 | 256.3
9 | Influenza and pneumonia(J09–J18) | 16,179 | 1.8 | 251.4
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 15,894 | 1.8 | 247.0
… | All other causes(residual) | 274,197 | 30.8 | 4,260.9
| All races, all origins, male, all ages^††^
… | All causes | 1,599,440 | 100.0 | 950.1
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 376,875 | 23.6 | 223.9
2 | Malignant neoplasms(C00–C97) | 325,806 | 20.4 | 193.5
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 129,755 | 8.1 | 77.1
4 | Cerebrovascular diseases(I60–I69) | 73,256 | 4.6 | 43.5
5 | Chronic lower respiratory diseases(J40–J47) | 67,880 | 4.2 | 40.3
6 | Diabetes mellitus(E10–E14) | 54,061 | 3.4 | 32.1
7 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 38,977 | 2.4 | 23.2
8 | Alzheimer disease(G30) | 37,241 | 2.3 | 22.1
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | 32,109 | 2.0 | 19.1
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 28,651 | 1.8 | 17.0
… | All other causes(residual) | 434,829 | 27.2 | 258.3
| All races, all origins, male, 1–4
… | All causes | 2,186 | 100.0 | 28.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 766 | 35.0 | 10.0
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 210 | 9.6 | 2.7
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 151 | 6.9 | 2.0
4 | Malignant neoplasms(C00–C97) | 148 | 6.8 | 1.9
5 | Influenza and pneumonia(J09–J18) | 69 | 3.2 | 0.9
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 61 | 2.8 | 0.8
7 | Certain conditions originating in the perinatal period(P00–P96) | 36 | 1.6 | 0.5
8 | Septicemia(A40–A41) | 33 | 1.5 | 0.4
9 | Cerebrovascular diseases(I60–I69) | 32 | 1.5 | 0.4
10 | Chronic lower respiratory diseases(J40–J47) | 24 | 1.1 | 0.3
… | All other causes(residual) | 656 | 30.0 | 8.6
| All races, all origins, male, 5–9
… | All causes | 1,386 | 100.0 | 13.4
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 421 | 30.4 | 4.1
2 | Malignant neoplasms(C00–C97) | 219 | 15.8 | 2.1
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 115 | 8.3 | 1.1
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 89 | 6.4 | 0.9
5 | Influenza and pneumonia(J09–J18) | 54 | 3.9 | 0.5
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 39 | 2.8 | 0.4
7 | Chronic lower respiratory diseases(J40–J47) | 33 | 2.4 | 0.3
8 | Cerebrovascular diseases(I60–I69) | 21 | 1.5 | 0.2
9 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 17 | 1.2 | 0.2
9 | Septicemia(A40–A41) | 17 | 1.2 | 0.2
… | All other causes(residual) | 361 | 26.0 | 3.5
| All races, all origins, male, 10–14
… | All causes | 2,015 | 100.0 | 18.8
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 517 | 25.7 | 4.8
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 255 | 12.7 | 2.4
3 | Malignant neoplasms(C00–C97) | 246 | 12.2 | 2.3
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 214 | 10.6 | 2.0
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 124 | 6.2 | 1.2
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 52 | 2.6 | 0.5
7 | Chronic lower respiratory diseases(J40–J47) | 46 | 2.3 | 0.4
8 | Cerebrovascular diseases(I60–I69) | 37 | 1.8 | 0.3
9 | Influenza and pneumonia(J09–J18) | 34 | 1.7 | 0.3
10 | Septicemia(A40–A41) | 22 | 1.1 | 0.2
… | All other causes(residual) | 468 | 23.2 | 4.4
| All races, all origins, male, 15–19
… | All causes | 8,238 | 100.0 | 71.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3,097 | 37.6 | 27.0
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 1,874 | 22.7 | 16.4
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,522 | 18.5 | 13.3
4 | Malignant neoplasms(C00–C97) | 379 | 4.6 | 3.3
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 203 | 2.5 | 1.8
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 135 | 1.6 | 1.2
7 | Legal intervention(Y35,Y89.0) | 61 | 0.7 | 0.5
8 | Diabetes mellitus(E10–E14) | 48 | 0.6 | 0.4
9 | Chronic lower respiratory diseases(J40–J47) | 47 | 0.6 | 0.4
10 | Influenza and pneumonia(J09–J18) | 40 | 0.5 | 0.3
… | All other causes(residual) | 832 | 10.1 | 7.3
| All races, all origins, male, 20–24
… | All causes | 13,690 | 100.0 | 119.5
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 5,576 | 40.7 | 48.7
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 3,104 | 22.7 | 27.1
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 2,195 | 16.0 | 19.2
4 | Malignant neoplasms(C00–C97) | 493 | 3.6 | 4.3
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 366 | 2.7 | 3.2
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 134 | 1.0 | 1.2
7 | Diabetes mellitus(E10–E14) | 108 | 0.8 | 0.9
8 | Chronic lower respiratory diseases(J40–J47) | 76 | 0.6 | 0.7
9 | Cerebrovascular diseases(I60–I69) | 62 | 0.5 | 0.5
10 | Influenza and pneumonia(J09–J18) | 58 | 0.4 | 0.5
… | All other causes(residual) | 1,518 | 11.1 | 13.3
| All races, all origins, male, 25–34
… | All causes | 40,651 | 100.0 | 172.8
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 16,959 | 41.7 | 72.1
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 6,472 | 15.9 | 27.5
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 4,049 | 10.0 | 17.2
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 2,391 | 5.9 | 10.2
5 | Malignant neoplasms(C00–C97) | 1,756 | 4.3 | 7.5
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 988 | 2.4 | 4.2
7 | Diabetes mellitus(E10–E14) | 654 | 1.6 | 2.8
8 | Human immunodeficiency virus (HIV) disease(B20–B24) | 317 | 0.8 | 1.3
9 | Cerebrovascular diseases(I60–I69) | 313 | 0.8 | 1.3
9 | Influenza and pneumonia(J09–J18) | 313 | 0.8 | 1.3
… | All other causes(residual) | 6,439 | 15.8 | 27.4
| All races, all origins, male, 35–44
… | All causes | 64,093 | 100.0 | 279.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 21,269 | 33.2 | 92.7
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 7,958 | 12.4 | 34.7
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 6,786 | 10.6 | 29.6
4 | Malignant neoplasms(C00–C97) | 5,104 | 8.0 | 22.2
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 3,349 | 5.2 | 14.6
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 3,168 | 4.9 | 13.8
7 | Diabetes mellitus(E10–E14) | 1,612 | 2.5 | 7.0
8 | Cerebrovascular diseases(I60–I69) | 1,218 | 1.9 | 5.3
9 | Influenza and pneumonia(J09–J18) | 592 | 0.9 | 2.6
10 | Human immunodeficiency virus (HIV) disease(B20–B24) | 580 | 0.9 | 2.5
… | All other causes(residual) | 12,457 | 19.4 | 54.3
| All races, all origins, male, 45–54
… | All causes | 98,643 | 100.0 | 485.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 20,906 | 21.2 | 102.9
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 18,185 | 18.4 | 89.5
3 | Malignant neoplasms(C00–C97) | 15,588 | 15.8 | 76.7
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 5,954 | 6.0 | 29.3
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 5,299 | 5.4 | 26.1
6 | Diabetes mellitus(E10–E14) | 4,270 | 4.3 | 21.0
7 | Cerebrovascular diseases(I60–I69) | 3,025 | 3.1 | 14.9
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 1,991 | 2.0 | 9.8
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,396 | 1.4 | 6.9
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,167 | 1.2 | 5.7
… | All other causes(residual) | 20,862 | 21.1 | 102.7
| All races, all origins, male, 55–64
… | All causes | 217,362 | 100.0 | 1,064.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 53,058 | 24.4 | 259.9
2 | Malignant neoplasms(C00–C97) | 51,948 | 23.9 | 254.5
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 20,680 | 9.5 | 101.3
4 | Diabetes mellitus(E10–E14) | 9,975 | 4.6 | 48.9
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 9,086 | 4.2 | 44.5
6 | Cerebrovascular diseases(I60–I69) | 7,837 | 3.6 | 38.4
7 | Chronic lower respiratory diseases(J40–J47) | 7,332 | 3.4 | 35.9
8 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 6,097 | 2.8 | 29.9
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 3,403 | 1.6 | 16.7
10 | Septicemia(A40–A41) | 2,922 | 1.3 | 14.3
… | All other causes(residual) | 45,024 | 20.7 | 220.5
| All races, all origins, male, 65 and older
… | All causes | 1,140,237 | 100.0 | 4,117.8
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 291,692 | 25.6 | 1,053.4
2 | Malignant neoplasms(C00–C97) | 249,898 | 21.9 | 902.5
3 | Cerebrovascular diseases(I60–I69) | 60,637 | 5.3 | 219.0
4 | Chronic lower respiratory diseases(J40–J47) | 58,635 | 5.1 | 211.8
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 41,611 | 3.6 | 150.3
6 | Diabetes mellitus(E10–E14) | 37,374 | 3.3 | 135.0
7 | Alzheimer disease(G30) | 36,573 | 3.2 | 132.1
8 | Parkinson disease(G20–G21) | 24,690 | 2.2 | 89.2
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 23,103 | 2.0 | 83.4
10 | Influenza and pneumonia(J09–J18) | 19,588 | 1.7 | 70.7
… | All other causes(residual) | 296,436 | 26.0 | 1,070.5
| All races, all origins, male, 65–74
… | All causes | 361,356 | 100.0 | 2,163.9
1 | Malignant neoplasms(C00–C97) | 99,547 | 27.5 | 596.1
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 87,664 | 24.3 | 524.9
3 | Chronic lower respiratory diseases(J40–J47) | 19,810 | 5.5 | 118.6
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 15,966 | 4.4 | 95.6
5 | Cerebrovascular diseases(I60–I69) | 15,299 | 4.2 | 91.6
6 | Diabetes mellitus(E10–E14) | 14,879 | 4.1 | 89.1
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 8,437 | 2.3 | 50.5
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 6,657 | 1.8 | 39.9
9 | Influenza and pneumonia(J09–J18) | 5,263 | 1.5 | 31.5
10 | Septicemia(A40–A41) | 5,196 | 1.4 | 31.1
… | All other causes(residual) | 82,638 | 22.9 | 494.8
| All races, all origins, male, 75–84
… | All causes | 424,609 | 100.0 | 4,950.6
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 102,043 | 24.0 | 1,189.7
2 | Malignant neoplasms(C00–C97) | 98,362 | 23.2 | 1,146.8
3 | Chronic lower respiratory diseases(J40–J47) | 24,171 | 5.7 | 281.8
4 | Cerebrovascular diseases(I60–I69) | 22,339 | 5.3 | 260.5
5 | Diabetes mellitus(E10–E14) | 14,400 | 3.4 | 167.9
6 | Alzheimer disease(G30) | 13,722 | 3.2 | 160.0
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 13,711 | 3.2 | 159.9
8 | Parkinson disease(G20–G21) | 12,095 | 2.8 | 141.0
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 8,779 | 2.1 | 102.4
10 | Influenza and pneumonia(J09–J18) | 7,123 | 1.7 | 83.0
… | All other causes(residual) | 107,864 | 25.4 | 1,257.6
| All races, all origins, male, 85 and older
… | All causes | 354,272 | 100.0 | 14,675.6
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 101,985 | 28.8 | 4,224.7
2 | Malignant neoplasms(C00–C97) | 51,989 | 14.7 | 2,153.6
3 | Cerebrovascular diseases(I60–I69) | 22,999 | 6.5 | 952.7
4 | Alzheimer disease(G30) | 19,026 | 5.4 | 788.1
5 | Chronic lower respiratory diseases(J40–J47) | 14,654 | 4.1 | 607.0
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 11,934 | 3.4 | 494.4
7 | Parkinson disease(G20–G21) | 8,287 | 2.3 | 343.3
8 | Diabetes mellitus(E10–E14) | 8,095 | 2.3 | 335.3
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 7,667 | 2.2 | 317.6
10 | Influenza and pneumonia(J09–J18) | 7,202 | 2.0 | 298.3
… | All other causes(residual) | 100,434 | 28.3 | 4,160.5
| All races, all origins, female, all ages^††^
… | All causes | 1,473,226 | 100.0 | 857.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 306,616 | 20.8 | 178.5
2 | Malignant neoplasms(C00–C97) | 294,070 | 20.0 | 171.2
3 | Cerebrovascular diseases(I60–I69) | 93,596 | 6.4 | 54.5
4 | Alzheimer disease(G30) | 78,781 | 5.3 | 45.9
5 | Chronic lower respiratory diseases(J40–J47) | 77,763 | 5.3 | 45.3
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 67,694 | 4.6 | 39.4
7 | Diabetes mellitus(E10–E14) | 40,384 | 2.7 | 23.5
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 26,430 | 1.8 | 15.4
9 | Influenza and pneumonia(J09–J18) | 23,500 | 1.6 | 13.7
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 22,459 | 1.5 | 13.1
… | All other causes(residual) | 441,933 | 30.0 | 257.3
| All races, all origins, female, 1–4
… | All causes | 1,657 | 100.0 | 22.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 486 | 29.3 | 6.6
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 192 | 11.6 | 2.6
3 | Malignant neoplasms(C00–C97) | 130 | 7.8 | 1.8
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 117 | 7.1 | 1.6
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 73 | 4.4 | 1.0
6 | Influenza and pneumonia(J09–J18) | 52 | 3.1 | 0.7
7 | Cerebrovascular diseases(I60–I69) | 30 | 1.8 | 0.4
8 | Septicemia(A40–A41) | 29 | 1.8 | 0.4
9 | Certain conditions originating in the perinatal period(P00–P96) | 24 | 1.4 | 0.3
10 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 22 | 1.3 | 0.3
… | All other causes(residual) | 502 | 30.3 | 6.8
| All races, all origins, female, 5–9
… | All causes | 1,146 | 100.0 | 11.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 298 | 26.0 | 3.0
2 | Malignant neoplasms(C00–C97) | 181 | 15.8 | 1.8
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 110 | 9.6 | 1.1
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 57 | 5.0 | 0.6
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 41 | 3.6 | 0.4
6 | Influenza and pneumonia(J09–J18) | 37 | 3.2 | 0.4
7 | Cerebrovascular diseases(I60–I69) | 28 | 2.4 | 0.3
8 | Chronic lower respiratory diseases(J40–J47) | 24 | 2.1 | 0.2
9 | Septicemia(A40–A41) | 19 | 1.7 | 0.2
10 | Anemias(D50–D64) | 11 | 1.0 | 0.1
… | All other causes(residual) | 340 | 29.7 | 3.4
| All races, all origins, female, 10–14
… | All causes | 1,393 | 100.0 | 13.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 278 | 20.0 | 2.7
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 232 | 16.7 | 2.3
3 | Malignant neoplasms(C00–C97) | 200 | 14.4 | 2.0
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 79 | 5.7 | 0.8
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 76 | 5.5 | 0.7
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 48 | 3.4 | 0.5
7 | Influenza and pneumonia(J09–J18) | 35 | 2.5 | 0.3
8 | Chronic lower respiratory diseases(J40–J47) | 33 | 2.4 | 0.3
9 | Cerebrovascular diseases(I60–I69) | 22 | 1.6 | 0.2
10 | Diabetes mellitus(E10–E14) | 19 | 1.4 | 0.2
… | All other causes(residual) | 371 | 26.6 | 3.6
| All races, all origins, female, 15–19
… | All causes | 3,168 | 100.0 | 29.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,138 | 35.9 | 10.4
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 584 | 18.4 | 5.4
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 274 | 8.6 | 2.5
4 | Malignant neoplasms(C00–C97) | 254 | 8.0 | 2.3
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 97 | 3.1 | 0.9
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 96 | 3.0 | 0.9
7 | Chronic lower respiratory diseases(J40–J47) | 35 | 1.1 | 0.3
8 | Influenza and pneumonia(J09–J18) | 34 | 1.1 | 0.3
9 | Diabetes mellitus(E10–E14) | 27 | 0.9 | 0.2
10 | Cerebrovascular diseases(I60–I69) | 25 | 0.8 | 0.2
10 | Pregnancy, childbirth and the puerperium(O00–O99) | 25 | 0.8 | 0.2
… | All other causes(residual) | 579 | 18.3 | 5.3
| All races, all origins, female, 20–24
… | All causes | 4,857 | 100.0 | 44.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,894 | 39.0 | 17.3
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 705 | 14.5 | 6.4
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 416 | 8.6 | 3.8
4 | Malignant neoplasms(C00–C97) | 295 | 6.1 | 2.7
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 166 | 3.4 | 1.5
6 | Pregnancy, childbirth and the puerperium(O00–O99) | 125 | 2.6 | 1.1
7 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 107 | 2.2 | 1.0
8 | Diabetes mellitus(E10–E14) | 67 | 1.4 | 0.6
9 | Chronic lower respiratory diseases(J40–J47) | 50 | 1.0 | 0.5
10 | Influenza and pneumonia(J09–J18) | 47 | 1.0 | 0.4
… | All other causes(residual) | 985 | 20.3 | 9.0
| All races, all origins, female, 25–34
… | All causes | 17,176 | 100.0 | 74.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 6,060 | 35.3 | 26.4
2 | Malignant neoplasms(C00–C97) | 1,903 | 11.1 | 8.3
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,521 | 8.9 | 6.6
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,120 | 6.5 | 4.9
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 828 | 4.8 | 3.6
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 603 | 3.5 | 2.6
7 | Pregnancy, childbirth and the puerperium(O00–O99) | 473 | 2.8 | 2.1
8 | Diabetes mellitus(E10–E14) | 397 | 2.3 | 1.7
9 | Cerebrovascular diseases(I60–I69) | 222 | 1.3 | 1.0
10 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 197 | 1.1 | 0.9
… | All other causes(residual) | 3,852 | 22.4 | 16.8
| All races, all origins, female, 35–44
… | All causes | 33,337 | 100.0 | 147.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 7,869 | 23.6 | 34.8
2 | Malignant neoplasms(C00–C97) | 6,479 | 19.4 | 28.7
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 3,649 | 10.9 | 16.2
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,840 | 5.5 | 8.1
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,728 | 5.2 | 7.7
6 | Diabetes mellitus(E10–E14) | 973 | 2.9 | 4.3
7 | Cerebrovascular diseases(I60–I69) | 868 | 2.6 | 3.8
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 788 | 2.4 | 3.5
9 | Influenza and pneumonia(J09–J18) | 434 | 1.3 | 1.9
10 | Septicemia(A40–A41) | 391 | 1.2 | 1.7
… | All other causes(residual) | 8,318 | 25.0 | 36.8
| All races, all origins, female, 45–54
… | All causes | 59,127 | 100.0 | 289.0
1 | Malignant neoplasms(C00–C97) | 16,863 | 28.5 | 82.4
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 8,718 | 14.7 | 42.6
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 7,056 | 11.9 | 34.5
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 3,015 | 5.1 | 14.7
5 | Diabetes mellitus(E10–E14) | 2,273 | 3.8 | 11.1
6 | Cerebrovascular diseases(I60–I69) | 2,167 | 3.7 | 10.6
7 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,723 | 2.9 | 8.4
8 | Chronic lower respiratory diseases(J40–J47) | 1,312 | 2.2 | 6.4
9 | Septicemia(A40–A41) | 1,020 | 1.7 | 5.0
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 941 | 1.6 | 4.6
… | All other causes(residual) | 14,039 | 23.7 | 68.6
| All races, all origins, female, 55–64
… | All causes | 140,834 | 100.0 | 662.9
1 | Malignant neoplasms(C00–C97) | 46,644 | 33.1 | 219.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 23,443 | 16.6 | 110.3
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 7,948 | 5.6 | 37.4
4 | Chronic lower respiratory diseases(J40–J47) | 7,781 | 5.5 | 36.6
5 | Diabetes mellitus(E10–E14) | 5,606 | 4.0 | 26.4
6 | Cerebrovascular diseases(I60–I69) | 5,385 | 3.8 | 25.3
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 5,175 | 3.7 | 24.4
8 | Septicemia(A40–A41) | 2,452 | 1.7 | 11.5
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 2,435 | 1.7 | 11.5
10 | Influenza and pneumonia(J09–J18) | 2,170 | 1.5 | 10.2
… | All other causes(residual) | 31,795 | 22.6 | 149.6
| All races, all origins, female, 65 and older
… | All causes | 1,201,363 | 100.0 | 3,587.3
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 269,136 | 22.4 | 803.6
2 | Malignant neoplasms(C00–C97) | 221,099 | 18.4 | 660.2
3 | Cerebrovascular diseases(I60–I69) | 84,765 | 7.1 | 253.1
4 | Alzheimer disease(G30) | 77,936 | 6.5 | 232.7
5 | Chronic lower respiratory diseases(J40–J47) | 67,995 | 5.7 | 203.0
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 34,088 | 2.8 | 101.8
7 | Diabetes mellitus(E10–E14) | 31,013 | 2.6 | 92.6
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 22,480 | 1.9 | 67.1
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 19,984 | 1.7 | 59.7
10 | Influenza and pneumonia(J09–J18) | 19,616 | 1.6 | 58.6
… | All other causes(residual) | 353,251 | 29.4 | 1,054.8
| All races, all origins, female, 65–74
… | All causes | 267,060 | 100.0 | 1,424.7
1 | Malignant neoplasms(C00–C97) | 81,793 | 30.6 | 436.3
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 48,471 | 18.1 | 258.6
3 | Chronic lower respiratory diseases(J40–J47) | 19,125 | 7.2 | 102.0
4 | Cerebrovascular diseases(I60–I69) | 12,844 | 4.8 | 68.5
5 | Diabetes mellitus(E10–E14) | 9,901 | 3.7 | 52.8
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 7,549 | 2.8 | 40.3
7 | Alzheimer disease(G30) | 5,513 | 2.1 | 29.4
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 5,377 | 2.0 | 28.7
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | 5,127 | 1.9 | 27.4
10 | Septicemia(A40–A41) | 4,729 | 1.8 | 25.2
… | All other causes(residual) | 66,631 | 24.9 | 355.5
| All races, all origins, female, 75–84
… | All causes | 398,335 | 100.0 | 3,714.8
1 | Malignant neoplasms(C00–C97) | 85,300 | 21.4 | 795.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 79,658 | 20.0 | 742.9
3 | Chronic lower respiratory diseases(J40–J47) | 26,842 | 6.7 | 250.3
4 | Cerebrovascular diseases(I60–I69) | 26,587 | 6.7 | 247.9
5 | Alzheimer disease(G30) | 23,642 | 5.9 | 220.5
6 | Diabetes mellitus(E10–E14) | 11,536 | 2.9 | 107.6
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 10,477 | 2.6 | 97.7
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 8,276 | 2.1 | 77.2
9 | Parkinson disease(G20–G21) | 6,669 | 1.7 | 62.2
10 | Influenza and pneumonia(J09–J18) | 6,424 | 1.6 | 59.9
… | All other causes(residual) | 112,924 | 28.3 | 1,053.1
| All races, all origins, female, 85 and older
… | All causes | 535,968 | 100.0 | 13,328.8
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 141,007 | 26.3 | 3,506.7
2 | Malignant neoplasms(C00–C97) | 54,006 | 10.1 | 1,343.1
3 | Alzheimer disease(G30) | 48,781 | 9.1 | 1,213.1
4 | Cerebrovascular diseases(I60–I69) | 45,334 | 8.5 | 1,127.4
5 | Chronic lower respiratory diseases(J40–J47) | 22,028 | 4.1 | 547.8
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 16,062 | 3.0 | 399.4
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 10,438 | 1.9 | 259.6
8 | Diabetes mellitus(E10–E14) | 9,576 | 1.8 | 238.1
9 | Nutritional deficiencies(E40–E64) | 9,476 | 1.8 | 235.7
10 | Influenza and pneumonia(J09–J18) | 8,977 | 1.7 | 223.2
… | All other causes(residual) | 170,283 | 31.8 | 4,234.7
| All races, Hispanic, both sexes, all ages^††^
… | All causes | 260,799 | 100.0 | 383.0
1 | Malignant neoplasms(C00–C97) | 51,120 | 19.6 | 75.1
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 47,679 | 18.3 | 70.0
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 26,105 | 10.0 | 38.3
4 | Cerebrovascular diseases(I60–I69) | 14,629 | 5.6 | 21.5
5 | Diabetes mellitus(E10–E14) | 12,070 | 4.6 | 17.7
6 | Alzheimer disease(G30) | 9,296 | 3.6 | 13.7
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 8,724 | 3.3 | 12.8
8 | Chronic lower respiratory diseases(J40–J47) | 5,709 | 2.2 | 8.4
9 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 5,382 | 2.1 | 7.9
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 5,255 | 2.0 | 7.7
… | All other causes(residual) | 74,830 | 28.7 | 109.9
| All races, Hispanic, both sexes, 1–4
… | All causes | 900 | 100.0 | 21.5
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 280 | 31.1 | 6.7
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 101 | 11.2 | 2.4
3 | Malignant neoplasms(C00–C97) | 73 | 8.1 | 1.7
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 62 | 6.9 | 1.5
5 | Influenza and pneumonia(J09–J18) | 32 | 3.6 | 0.8
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 31 | 3.4 | 0.7
7 | Cerebrovascular diseases(I60–I69) | 20 | 2.2 | 0.5
8 | Septicemia(A40–A41) | 15 | 1.7 | 0.4
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
9 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
… | All other causes(residual) | 274 | 30.4 | 6.5
| All races, Hispanic, both sexes, 5–9
… | All causes | 586 | 100.0 | 10.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 158 | 27.0 | 2.9
2 | Malignant neoplasms(C00–C97) | 107 | 18.3 | 2.0
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 55 | 9.4 | 1.0
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 25 | 4.3 | 0.5
5 | Influenza and pneumonia(J09–J18) | 23 | 3.9 | 0.4
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 18 | 3.1 | 0.3
7 | Cerebrovascular diseases(I60–I69) | 10 | 1.7 | 0.2
8 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
8 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 168 | 28.7 | 3.1
| All races, Hispanic, both sexes, 10–14
… | All causes | 807 | 100.0 | 14.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 189 | 23.4 | 3.4
2 | Malignant neoplasms(C00–C97) | 132 | 16.4 | 2.4
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 95 | 11.8 | 1.7
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 65 | 8.1 | 1.2
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 48 | 5.9 | 0.9
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 22 | 2.7 | 0.4
7 | Influenza and pneumonia(J09–J18) | 19 | 2.4 | 0.3
8 | Cerebrovascular diseases(I60–I69) | 17 | 2.1 | 0.3
8 | Chronic lower respiratory diseases(J40–J47) | 17 | 2.1 | 0.3
10 | Septicemia(A40–A41) | 10 | 1.2 | 0.2
… | All other causes(residual) | 193 | 23.9 | 3.5
| All races, Hispanic, both sexes, 15–19
… | All causes | 2,820 | 100.0 | 47.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,235 | 43.8 | 20.9
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 451 | 16.0 | 7.6
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 430 | 15.2 | 7.3
4 | Malignant neoplasms(C00–C97) | 204 | 7.2 | 3.4
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 53 | 1.9 | 0.9
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 52 | 1.8 | 0.9
7 | Legal intervention(Y35,Y89.0) | 22 | 0.8 | 0.4
8 | Chronic lower respiratory diseases(J40–J47) | 16 | 0.6 | 0.3
9 | Cerebrovascular diseases(I60–I69) | 15 | 0.5 | 0.3
9 | Influenza and pneumonia(J09–J18) | 15 | 0.5 | 0.3
… | All other causes(residual) | 327 | 11.6 | 5.5
| All races, Hispanic, both sexes, 20–24
… | All causes | 4,566 | 100.0 | 82.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 2,152 | 47.1 | 38.7
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 766 | 16.8 | 13.8
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 533 | 11.7 | 9.6
4 | Malignant neoplasms(C00–C97) | 231 | 5.1 | 4.2
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 110 | 2.4 | 2.0
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 42 | 0.9 | 0.8
7 | Pregnancy, childbirth and the puerperium(O00–O99) | 37 | 0.8 | 0.7
8 | Cerebrovascular diseases(I60–I69) | 34 | 0.7 | 0.6
9 | Influenza and pneumonia(J09–J18) | 30 | 0.7 | 0.5
10 | Chronic lower respiratory diseases(J40–J47) | 27 | 0.6 | 0.5
… | All other causes(residual) | 604 | 13.2 | 10.9
| All races, Hispanic, both sexes, 25–34
… | All causes | 12,038 | 100.0 | 115.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 5,322 | 44.2 | 50.8
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,328 | 11.0 | 12.7
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 998 | 8.3 | 9.5
4 | Malignant neoplasms(C00–C97) | 919 | 7.6 | 8.8
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 537 | 4.5 | 5.1
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 435 | 3.6 | 4.2
7 | Diabetes mellitus(E10–E14) | 148 | 1.2 | 1.4
8 | Cerebrovascular diseases(I60–I69) | 127 | 1.1 | 1.2
9 | Human immunodeficiency virus (HIV) disease(B20–B24) | 105 | 0.9 | 1.0
10 | Influenza and pneumonia(J09–J18) | 100 | 0.8 | 1.0
… | All other causes(residual) | 2,019 | 16.8 | 19.3
| All races, Hispanic, both sexes, 35–44
… | All causes | 16,251 | 100.0 | 168.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 5,155 | 31.7 | 53.3
2 | Malignant neoplasms(C00–C97) | 2,179 | 13.4 | 22.5
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,452 | 8.9 | 15.0
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,117 | 6.9 | 11.6
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,110 | 6.8 | 11.5
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 834 | 5.1 | 8.6
7 | Cerebrovascular diseases(I60–I69) | 433 | 2.7 | 4.5
8 | Diabetes mellitus(E10–E14) | 419 | 2.6 | 4.3
9 | Influenza and pneumonia(J09–J18) | 177 | 1.1 | 1.8
10 | Human immunodeficiency virus (HIV) disease(B20–B24) | 153 | 0.9 | 1.6
… | All other causes(residual) | 3,222 | 19.8 | 33.3
| All races, Hispanic, both sexes, 45–54
… | All causes | 22,851 | 100.0 | 278.5
1 | Malignant neoplasms(C00–C97) | 4,973 | 21.8 | 60.6
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3,909 | 17.1 | 47.6
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 3,482 | 15.2 | 42.4
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,728 | 7.6 | 21.1
5 | Diabetes mellitus(E10–E14) | 1,130 | 4.9 | 13.8
6 | Cerebrovascular diseases(I60–I69) | 981 | 4.3 | 12.0
7 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 760 | 3.3 | 9.3
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 449 | 2.0 | 5.5
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 407 | 1.8 | 5.0
10 | Septicemia(A40–A41) | 319 | 1.4 | 3.9
… | All other causes(residual) | 4,713 | 20.6 | 57.4
| All races, Hispanic, both sexes, 55–64
… | All causes | 35,988 | 100.0 | 582.9
1 | Malignant neoplasms(C00–C97) | 9,855 | 27.4 | 159.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 6,825 | 19.0 | 110.5
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3,099 | 8.6 | 50.2
4 | Diabetes mellitus(E10–E14) | 2,383 | 6.6 | 38.6
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 2,221 | 6.2 | 36.0
6 | Cerebrovascular diseases(I60–I69) | 1,602 | 4.5 | 25.9
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 772 | 2.1 | 12.5
8 | Septicemia(A40–A41) | 552 | 1.5 | 8.9
9 | Influenza and pneumonia(J09–J18) | 547 | 1.5 | 8.9
10 | Chronic lower respiratory diseases(J40–J47) | 504 | 1.4 | 8.2
… | All other causes(residual) | 7,628 | 21.2 | 123.5
| All races, Hispanic, both sexes, 65 and older
… | All causes | 158,949 | 100.0 | 2,661.3
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 35,090 | 22.1 | 587.5
2 | Malignant neoplasms(C00–C97) | 32,440 | 20.4 | 543.2
3 | Cerebrovascular diseases(I60–I69) | 11,373 | 7.2 | 190.4
4 | Alzheimer disease(G30) | 9,142 | 5.8 | 153.1
5 | Diabetes mellitus(E10–E14) | 7,947 | 5.0 | 133.1
6 | Chronic lower respiratory diseases(J40–J47) | 4,851 | 3.1 | 81.2
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,399 | 2.8 | 73.7
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 3,856 | 2.4 | 64.6
9 | Influenza and pneumonia(J09–J18) | 3,209 | 2.0 | 53.7
10 | Chronic liver disease and cirrhosis(K70,K73–K74) | 3,206 | 2.0 | 53.7
… | All other causes(residual) | 43,436 | 27.3 | 727.3
| All races, Hispanic, both sexes, 65–74
… | All causes | 47,137 | 100.0 | 1,274.0
1 | Malignant neoplasms(C00–C97) | 13,412 | 28.5 | 362.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 9,445 | 20.0 | 255.3
3 | Diabetes mellitus(E10–E14) | 3,100 | 6.6 | 83.8
4 | Cerebrovascular diseases(I60–I69) | 2,432 | 5.2 | 65.7
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,899 | 4.0 | 51.3
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,781 | 3.8 | 48.1
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,253 | 2.7 | 33.9
8 | Chronic lower respiratory diseases(J40–J47) | 1,151 | 2.4 | 31.1
9 | Influenza and pneumonia(J09–J18) | 872 | 1.8 | 23.6
10 | Septicemia(A40–A41) | 795 | 1.7 | 21.5
… | All other causes(residual) | 10,997 | 23.3 | 297.2
| All races, Hispanic, both sexes, 75–84
… | All causes | 53,593 | 100.0 | 3,166.7
1 | Malignant neoplasms(C00–C97) | 11,986 | 22.4 | 708.2
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 11,375 | 21.2 | 672.1
3 | Cerebrovascular diseases(I60–I69) | 3,788 | 7.1 | 223.8
4 | Diabetes mellitus(E10–E14) | 2,855 | 5.3 | 168.7
5 | Alzheimer disease(G30) | 2,644 | 4.9 | 156.2
6 | Chronic lower respiratory diseases(J40–J47) | 1,730 | 3.2 | 102.2
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,427 | 2.7 | 84.3
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,335 | 2.5 | 78.9
9 | Influenza and pneumonia(J09–J18) | 1,093 | 2.0 | 64.6
10 | Parkinson disease(G20–G21) | 1,040 | 1.9 | 61.5
… | All other causes(residual) | 14,320 | 26.7 | 846.1
| All races, Hispanic, both sexes, 85 and older
… | All causes | 58,219 | 100.0 | 10,036.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 14,270 | 24.5 | 2,460.0
2 | Malignant neoplasms(C00–C97) | 7,042 | 12.1 | 1,214.0
3 | Alzheimer disease(G30) | 5,777 | 9.9 | 995.9
4 | Cerebrovascular diseases(I60–I69) | 5,153 | 8.9 | 888.3
5 | Diabetes mellitus(E10–E14) | 1,992 | 3.4 | 343.4
6 | Chronic lower respiratory diseases(J40–J47) | 1,970 | 3.4 | 339.6
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,296 | 2.2 | 223.4
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,283 | 2.2 | 221.2
9 | Influenza and pneumonia(J09–J18) | 1,244 | 2.1 | 214.5
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,176 | 2.0 | 202.7
… | All other causes(residual) | 17,016 | 29.2 | 2,933.4
| All races, Hispanic, male, all ages^††^
… | All causes | 145,230 | 100.0 | 421.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 27,479 | 18.9 | 79.7
2 | Malignant neoplasms(C00–C97) | 26,277 | 18.1 | 76.3
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 19,790 | 13.6 | 57.4
4 | Cerebrovascular diseases(I60–I69) | 6,899 | 4.8 | 20.0
5 | Diabetes mellitus(E10–E14) | 6,810 | 4.7 | 19.8
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 5,824 | 4.0 | 16.9
7 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 4,350 | 3.0 | 12.6
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 3,097 | 2.1 | 9.0
9 | Alzheimer disease(G30) | 2,909 | 2.0 | 8.4
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 2,897 | 2.0 | 8.4
… | All other causes(residual) | 38,898 | 26.8 | 112.9
| All races, Hispanic, male, 1–4
… | All causes | 481 | 100.0 | 22.5
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 160 | 33.3 | 7.5
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 47 | 9.8 | 2.2
3 | Malignant neoplasms(C00–C97) | 40 | 8.3 | 1.9
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 33 | 6.9 | 1.5
5 | Influenza and pneumonia(J09–J18) | 17 | 3.5 | 0.8
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 11 | 2.3 | 0.5
7 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
8 | Septicemia(A40–A41) | §§ | §§ | §§
8 | Complications of medical and surgical care(Y40–Y84,Y88) | §§ | §§ | §§
10 | COVID-19(*U07.1) | §§ | §§ | §§
10 | Certain conditions originating in the perinatal period(P00–P96) | §§ | §§ | §§
10 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
… | All other causes(residual) | 148 | 30.8 | 6.9
| All races, Hispanic, male, 5–9
… | All causes | 319 | 100.0 | 11.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 99 | 31.0 | 3.6
2 | Malignant neoplasms(C00–C97) | 57 | 17.9 | 2.1
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 26 | 8.2 | 1.0
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 15 | 4.7 | 0.5
5 | Influenza and pneumonia(J09–J18) | 12 | 3.8 | 0.4
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
7 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
7 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
7 | Meningitis(G00,G03) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
10 | Diseases of appendix(K35–K38) | §§ | §§ | §§
10 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
10 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
10 | Certain conditions originating in the perinatal period(P00–P96) | §§ | §§ | §§
… | All other causes(residual) | 80 | 25.1 | 2.9
| All races, Hispanic, male, 10–14
… | All causes | 468 | 100.0 | 16.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 110 | 23.5 | 3.9
2 | Malignant neoplasms(C00–C97) | 73 | 15.6 | 2.6
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 50 | 10.7 | 1.8
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 50 | 10.7 | 1.8
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 29 | 6.2 | 1.0
6 | Cerebrovascular diseases(I60–I69) | 12 | 2.6 | 0.4
7 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
7 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
9 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 116 | 24.8 | 4.1
| All races, Hispanic, male, 15–19
… | All causes | 2,075 | 100.0 | 68.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 933 | 45.0 | 30.7
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 409 | 19.7 | 13.4
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 281 | 13.5 | 9.2
4 | Malignant neoplasms(C00–C97) | 127 | 6.1 | 4.2
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 38 | 1.8 | 1.2
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 31 | 1.5 | 1.0
7 | Legal intervention(Y35,Y89.0) | 22 | 1.1 | 0.7
8 | Cerebrovascular diseases(I60–I69) | 13 | 0.6 | 0.4
9 | Influenza and pneumonia(J09–J18) | 11 | 0.5 | 0.4
10 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
… | All other causes(residual) | 201 | 9.7 | 6.6
| All races, Hispanic, male, 20–24
… | All causes | 3,486 | 100.0 | 122.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,702 | 48.8 | 59.6
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 626 | 18.0 | 21.9
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 449 | 12.9 | 15.7
4 | Malignant neoplasms(C00–C97) | 158 | 4.5 | 5.5
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 81 | 2.3 | 2.8
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 24 | 0.7 | 0.8
7 | Cerebrovascular diseases(I60–I69) | 22 | 0.6 | 0.8
8 | Influenza and pneumonia(J09–J18) | 17 | 0.5 | 0.6
9 | Chronic lower respiratory diseases(J40–J47) | 16 | 0.5 | 0.6
10 | Legal intervention(Y35,Y89.0) | 14 | 0.4 | 0.5
… | All other causes(residual) | 377 | 10.8 | 13.2
| All races, Hispanic, male, 25–34
… | All causes | 9,058 | 100.0 | 168.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,293 | 47.4 | 79.9
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,105 | 12.2 | 20.6
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 839 | 9.3 | 15.6
4 | Malignant neoplasms(C00–C97) | 459 | 5.1 | 8.5
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 407 | 4.5 | 7.6
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 304 | 3.4 | 5.7
7 | Human immunodeficiency virus (HIV) disease(B20–B24) | 91 | 1.0 | 1.7
8 | Diabetes mellitus(E10–E14) | 86 | 0.9 | 1.6
9 | Cerebrovascular diseases(I60–I69) | 77 | 0.9 | 1.4
10 | Influenza and pneumonia(J09–J18) | 65 | 0.7 | 1.2
… | All other causes(residual) | 1,332 | 14.7 | 24.8
| All races, Hispanic, male, 35–44
… | All causes | 11,636 | 100.0 | 230.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,183 | 35.9 | 82.8
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,132 | 9.7 | 22.4
3 | Malignant neoplasms(C00–C97) | 950 | 8.2 | 18.8
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 911 | 7.8 | 18.0
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 830 | 7.1 | 16.4
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 680 | 5.8 | 13.5
7 | Cerebrovascular diseases(I60–I69) | 308 | 2.6 | 6.1
8 | Diabetes mellitus(E10–E14) | 271 | 2.3 | 5.4
9 | Human immunodeficiency virus (HIV) disease(B20–B24) | 131 | 1.1 | 2.6
10 | Influenza and pneumonia(J09–J18) | 111 | 1.0 | 2.2
… | All other causes(residual) | 2,129 | 18.3 | 42.1
| All races, Hispanic, male, 45–54
… | All causes | 15,410 | 100.0 | 369.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3,173 | 20.6 | 76.0
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 2,710 | 17.6 | 64.9
3 | Malignant neoplasms(C00–C97) | 2,263 | 14.7 | 54.2
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,273 | 8.3 | 30.5
5 | Diabetes mellitus(E10–E14) | 795 | 5.2 | 19.0
6 | Cerebrovascular diseases(I60–I69) | 639 | 4.1 | 15.3
7 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 627 | 4.1 | 15.0
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 366 | 2.4 | 8.8
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 260 | 1.7 | 6.2
10 | Septicemia(A40–A41) | 201 | 1.3 | 4.8
… | All other causes(residual) | 3,103 | 20.1 | 74.3
| All races, Hispanic, male, 55–64
… | All causes | 22,851 | 100.0 | 741.7
1 | Malignant neoplasms(C00–C97) | 5,135 | 22.5 | 166.7
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 4,970 | 21.7 | 161.3
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 2,469 | 10.8 | 80.1
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,605 | 7.0 | 52.1
5 | Diabetes mellitus(E10–E14) | 1,519 | 6.6 | 49.3
6 | Cerebrovascular diseases(I60–I69) | 1,009 | 4.4 | 32.7
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 474 | 2.1 | 15.4
8 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 400 | 1.8 | 13.0
9 | Influenza and pneumonia(J09–J18) | 345 | 1.5 | 11.2
10 | Septicemia(A40–A41) | 316 | 1.4 | 10.3
… | All other causes(residual) | 4,609 | 20.2 | 149.6
| All races, Hispanic, male, 65 and older
… | All causes | 76,742 | 100.0 | 2,869.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 18,085 | 23.6 | 676.2
2 | Malignant neoplasms(C00–C97) | 17,010 | 22.2 | 636.0
3 | Cerebrovascular diseases(I60–I69) | 4,801 | 6.3 | 179.5
4 | Diabetes mellitus(E10–E14) | 4,115 | 5.4 | 153.9
5 | Alzheimer disease(G30) | 2,841 | 3.7 | 106.2
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 2,571 | 3.4 | 96.1
7 | Chronic lower respiratory diseases(J40–J47) | 2,365 | 3.1 | 88.4
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 2,033 | 2.6 | 76.0
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,796 | 2.3 | 67.2
10 | Influenza and pneumonia(J09–J18) | 1,567 | 2.0 | 58.6
… | All other causes(residual) | 19,558 | 25.5 | 731.3
| All races, Hispanic, male, 65–74
… | All causes | 27,535 | 100.0 | 1,586.8
1 | Malignant neoplasms(C00–C97) | 7,368 | 26.8 | 424.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 6,140 | 22.3 | 353.8
3 | Diabetes mellitus(E10–E14) | 1,804 | 6.6 | 104.0
4 | Cerebrovascular diseases(I60–I69) | 1,378 | 5.0 | 79.4
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,266 | 4.6 | 73.0
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,189 | 4.3 | 68.5
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 724 | 2.6 | 41.7
8 | Chronic lower respiratory diseases(J40–J47) | 664 | 2.4 | 38.3
9 | Influenza and pneumonia(J09–J18) | 492 | 1.8 | 28.4
10 | Septicemia(A40–A41) | 431 | 1.6 | 24.8
… | All other causes(residual) | 6,079 | 22.1 | 350.3
| All races, Hispanic, male, 75–84
… | All causes | 26,898 | 100.0 | 3,712.6
1 | Malignant neoplasms(C00–C97) | 6,292 | 23.4 | 868.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 6,143 | 22.8 | 847.9
3 | Cerebrovascular diseases(I60–I69) | 1,739 | 6.5 | 240.0
4 | Diabetes mellitus(E10–E14) | 1,452 | 5.4 | 200.4
5 | Alzheimer disease(G30) | 942 | 3.5 | 130.0
6 | Chronic lower respiratory diseases(J40–J47) | 874 | 3.2 | 120.6
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 766 | 2.8 | 105.7
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 748 | 2.8 | 103.2
9 | Parkinson disease(G20–G21) | 639 | 2.4 | 88.2
10 | Influenza and pneumonia(J09–J18) | 555 | 2.1 | 76.6
… | All other causes(residual) | 6,748 | 25.1 | 931.4
| All races, Hispanic, male, 85 and older
… | All causes | 22,309 | 100.0 | 10,388.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 5,802 | 26.0 | 2,701.8
2 | Malignant neoplasms(C00–C97) | 3,350 | 15.0 | 1,560.0
3 | Cerebrovascular diseases(I60–I69) | 1,684 | 7.5 | 784.2
4 | Alzheimer disease(G30) | 1,581 | 7.1 | 736.2
5 | Diabetes mellitus(E10–E14) | 859 | 3.9 | 400.0
6 | Chronic lower respiratory diseases(J40–J47) | 827 | 3.7 | 385.1
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 561 | 2.5 | 261.2
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 539 | 2.4 | 251.0
9 | Influenza and pneumonia(J09–J18) | 520 | 2.3 | 242.1
10 | Parkinson disease(G20–G21) | 498 | 2.2 | 231.9
… | All other causes(residual) | 6,088 | 27.3 | 2,835.0
| All races, Hispanic, female, all ages^††^
… | All causes | 115,569 | 100.0 | 343.7
1 | Malignant neoplasms(C00–C97) | 24,843 | 21.5 | 73.9
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 20,200 | 17.5 | 60.1
3 | Cerebrovascular diseases(I60–I69) | 7,730 | 6.7 | 23.0
4 | Alzheimer disease(G30) | 6,387 | 5.5 | 19.0
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 6,315 | 5.5 | 18.8
6 | Diabetes mellitus(E10–E14) | 5,260 | 4.6 | 15.6
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 2,900 | 2.5 | 8.6
8 | Chronic lower respiratory diseases(J40–J47) | 2,895 | 2.5 | 8.6
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 2,358 | 2.0 | 7.0
10 | Influenza and pneumonia(J09–J18) | 2,122 | 1.8 | 6.3
… | All other causes(residual) | 34,559 | 29.9 | 102.8
| All races, Hispanic, female, 1–4
… | All causes | 419 | 100.0 | 20.4
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 120 | 28.6 | 5.8
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 54 | 12.9 | 2.6
3 | Malignant neoplasms(C00–C97) | 33 | 7.9 | 1.6
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 29 | 6.9 | 1.4
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 20 | 4.8 | 1.0
6 | Influenza and pneumonia(J09–J18) | 15 | 3.6 | 0.7
7 | Cerebrovascular diseases(I60–I69) | 12 | 2.9 | 0.6
8 | Septicemia(A40–A41) | 11 | 2.6 | 0.5
9 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
… | All other causes(residual) | 117 | 27.9 | 5.7
| All races, Hispanic, female, 5–9
… | All causes | 267 | 100.0 | 10.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 59 | 22.1 | 2.2
2 | Malignant neoplasms(C00–C97) | 50 | 18.7 | 1.9
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 29 | 10.9 | 1.1
4 | Influenza and pneumonia(J09–J18) | 11 | 4.1 | 0.4
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 10 | 3.7 | 0.4
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 10 | 3.7 | 0.4
7 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
8 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
8 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
8 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 78 | 29.2 | 3.0
| All races, Hispanic, female, 10–14
… | All causes | 339 | 100.0 | 12.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 79 | 23.3 | 2.9
2 | Malignant neoplasms(C00–C97) | 59 | 17.4 | 2.2
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 45 | 13.3 | 1.7
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 19 | 5.6 | 0.7
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 15 | 4.4 | 0.6
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 14 | 4.1 | 0.5
7 | Influenza and pneumonia(J09–J18) | 12 | 3.5 | 0.4
8 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
9 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
9 | COVID-19(*U07.1) | §§ | §§ | §§
9 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 72 | 21.2 | 2.7
| All races, Hispanic, female, 15–19
… | All causes | 745 | 100.0 | 25.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 302 | 40.5 | 10.5
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 149 | 20.0 | 5.2
3 | Malignant neoplasms(C00–C97) | 77 | 10.3 | 2.7
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 42 | 5.6 | 1.5
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 21 | 2.8 | 0.7
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 15 | 2.0 | 0.5
7 | Pregnancy, childbirth and the puerperium(O00–O99) | 12 | 1.6 | 0.4
8 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
9 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
10 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
… | All other causes(residual) | 111 | 14.9 | 3.9
| All races, Hispanic, female, 20–24
… | All causes | 1,080 | 100.0 | 39.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 450 | 41.7 | 16.6
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 140 | 13.0 | 5.2
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 84 | 7.8 | 3.1
4 | Malignant neoplasms(C00–C97) | 73 | 6.8 | 2.7
5 | Pregnancy, childbirth and the puerperium(O00–O99) | 37 | 3.4 | 1.4
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 29 | 2.7 | 1.1
7 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 18 | 1.7 | 0.7
8 | Influenza and pneumonia(J09–J18) | 13 | 1.2 | 0.5
9 | Cerebrovascular diseases(I60–I69) | 12 | 1.1 | 0.4
10 | Chronic lower respiratory diseases(J40–J47) | 11 | 1.0 | 0.4
… | All other causes(residual) | 213 | 19.7 | 7.9
| All races, Hispanic, female, 25–34
… | All causes | 2,980 | 100.0 | 58.4
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,029 | 34.5 | 20.2
2 | Malignant neoplasms(C00–C97) | 460 | 15.4 | 9.0
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 223 | 7.5 | 4.4
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 159 | 5.3 | 3.1
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 131 | 4.4 | 2.6
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 130 | 4.4 | 2.5
7 | Pregnancy, childbirth and the puerperium(O00–O99) | 79 | 2.7 | 1.5
8 | Diabetes mellitus(E10–E14) | 62 | 2.1 | 1.2
9 | Cerebrovascular diseases(I60–I69) | 50 | 1.7 | 1.0
10 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 41 | 1.4 | 0.8
… | All other causes(residual) | 616 | 20.7 | 12.1
| All races, Hispanic, female, 35–44
… | All causes | 4,615 | 100.0 | 100.0
1 | Malignant neoplasms(C00–C97) | 1,229 | 26.6 | 26.6
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 972 | 21.1 | 21.1
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 320 | 6.9 | 6.9
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 280 | 6.1 | 6.1
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 206 | 4.5 | 4.5
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 154 | 3.3 | 3.3
7 | Diabetes mellitus(E10–E14) | 148 | 3.2 | 3.2
8 | Cerebrovascular diseases(I60–I69) | 125 | 2.7 | 2.7
9 | Influenza and pneumonia(J09–J18) | 66 | 1.4 | 1.4
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 55 | 1.2 | 1.2
… | All other causes(residual) | 1,060 | 23.0 | 23.0
| All races, Hispanic, female, 45–54
… | All causes | 7,441 | 100.0 | 184.6
1 | Malignant neoplasms(C00–C97) | 2,710 | 36.4 | 67.2
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 772 | 10.4 | 19.2
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 736 | 9.9 | 18.3
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 455 | 6.1 | 11.3
5 | Cerebrovascular diseases(I60–I69) | 342 | 4.6 | 8.5
6 | Diabetes mellitus(E10–E14) | 335 | 4.5 | 8.3
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 147 | 2.0 | 3.6
8 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 133 | 1.8 | 3.3
9 | Septicemia(A40–A41) | 118 | 1.6 | 2.9
10 | Influenza and pneumonia(J09–J18) | 111 | 1.5 | 2.8
… | All other causes(residual) | 1,582 | 21.3 | 39.3
| All races, Hispanic, female, 55–64
… | All causes | 13,137 | 100.0 | 424.7
1 | Malignant neoplasms(C00–C97) | 4,720 | 35.9 | 152.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,855 | 14.1 | 60.0
3 | Diabetes mellitus(E10–E14) | 864 | 6.6 | 27.9
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 630 | 4.8 | 20.4
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 616 | 4.7 | 19.9
6 | Cerebrovascular diseases(I60–I69) | 593 | 4.5 | 19.2
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 298 | 2.3 | 9.6
8 | Chronic lower respiratory diseases(J40–J47) | 248 | 1.9 | 8.0
9 | Septicemia(A40–A41) | 236 | 1.8 | 7.6
10 | Influenza and pneumonia(J09–J18) | 202 | 1.5 | 6.5
… | All other causes(residual) | 2,875 | 21.9 | 92.9
| All races, Hispanic, female, 65 and older
… | All causes | 82,207 | 100.0 | 2,492.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 17,005 | 20.7 | 515.6
2 | Malignant neoplasms(C00–C97) | 15,430 | 18.8 | 467.9
3 | Cerebrovascular diseases(I60–I69) | 6,572 | 8.0 | 199.3
4 | Alzheimer disease(G30) | 6,301 | 7.7 | 191.1
5 | Diabetes mellitus(E10–E14) | 3,832 | 4.7 | 116.2
6 | Chronic lower respiratory diseases(J40–J47) | 2,486 | 3.0 | 75.4
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,828 | 2.2 | 55.4
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,823 | 2.2 | 55.3
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,667 | 2.0 | 50.5
10 | Influenza and pneumonia(J09–J18) | 1,642 | 2.0 | 49.8
… | All other causes(residual) | 23,621 | 28.7 | 716.2
| All races, Hispanic, female, 65–74
… | All causes | 19,602 | 100.0 | 997.7
1 | Malignant neoplasms(C00–C97) | 6,044 | 30.8 | 307.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 3,305 | 16.9 | 168.2
3 | Diabetes mellitus(E10–E14) | 1,296 | 6.6 | 66.0
4 | Cerebrovascular diseases(I60–I69) | 1,054 | 5.4 | 53.6
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 710 | 3.6 | 36.1
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 529 | 2.7 | 26.9
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 515 | 2.6 | 26.2
8 | Chronic lower respiratory diseases(J40–J47) | 487 | 2.5 | 24.8
9 | Alzheimer disease(G30) | 403 | 2.1 | 20.5
10 | Influenza and pneumonia(J09–J18) | 380 | 1.9 | 19.3
… | All other causes(residual) | 4,879 | 24.9 | 248.3
| All races, Hispanic, female, 75–84
… | All causes | 26,695 | 100.0 | 2,758.1
1 | Malignant neoplasms(C00–C97) | 5,694 | 21.3 | 588.3
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 5,232 | 19.6 | 540.6
3 | Cerebrovascular diseases(I60–I69) | 2,049 | 7.7 | 211.7
4 | Alzheimer disease(G30) | 1,702 | 6.4 | 175.8
5 | Diabetes mellitus(E10–E14) | 1,403 | 5.3 | 145.0
6 | Chronic lower respiratory diseases(J40–J47) | 856 | 3.2 | 88.4
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 679 | 2.5 | 70.2
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 569 | 2.1 | 58.8
9 | Influenza and pneumonia(J09–J18) | 538 | 2.0 | 55.6
10 | Chronic liver disease and cirrhosis(K70,K73–K74) | 512 | 1.9 | 52.9
… | All other causes(residual) | 7,461 | 27.9 | 770.9
| All races, Hispanic, female, 85 and older
… | All causes | 35,910 | 100.0 | 9,829.6
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 8,468 | 23.6 | 2,317.9
2 | Alzheimer disease(G30) | 4,196 | 11.7 | 1,148.6
3 | Malignant neoplasms(C00–C97) | 3,692 | 10.3 | 1,010.6
4 | Cerebrovascular diseases(I60–I69) | 3,469 | 9.7 | 949.6
5 | Chronic lower respiratory diseases(J40–J47) | 1,143 | 3.2 | 312.9
6 | Diabetes mellitus(E10–E14) | 1,133 | 3.2 | 310.1
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 846 | 2.4 | 231.6
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 744 | 2.1 | 203.7
9 | Influenza and pneumonia(J09–J18) | 724 | 2.0 | 198.2
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 615 | 1.7 | 168.3
… | All other causes(residual) | 10,880 | 30.3 | 2,978.2
| American Indian and Alaska Native, non-Hispanic, both sexes, all ages^††^
… | All causes | 20,924 | 100.0 | 856.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 3,688 | 17.6 | 151.0
2 | Malignant neoplasms(C00–C97) | 3,229 | 15.4 | 132.2
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 2,704 | 12.9 | 110.7
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,287 | 6.2 | 52.7
5 | Diabetes mellitus(E10–E14) | 1,104 | 5.3 | 45.2
6 | Chronic lower respiratory diseases(J40–J47) | 829 | 4.0 | 33.9
7 | Cerebrovascular diseases(I60–I69) | 782 | 3.7 | 32.0
8 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 545 | 2.6 | 22.3
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 384 | 1.8 | 15.7
10 | Alzheimer disease(G30) | 365 | 1.7 | 14.9
… | All other causes(residual) | 6,007 | 28.7 | 245.9
| American Indian and Alaska Native, non-Hispanic, both sexes, 1–4
… | All causes | 52 | 100.0 | 52.4
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 22 | 42.3 | 22.2
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
2 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
5 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
6 | Septicemia(A40–A41) | §§ | §§ | §§
6 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
… | All other causes(residual) | 14 | 26.9 | 14.1
| American Indian and Alaska Native, non-Hispanic, both sexes, 5–9
… | All causes | 38 | 100.0 | 25.4
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 14 | 36.8 | 9.3
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
5 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
5 | COVID-19(*U07.1) | §§ | §§ | §§
5 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
5 | Certain conditions originating in the perinatal period(P00–P96) | §§ | §§ | §§
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| American Indian and Alaska Native, non-Hispanic, both sexes, 10–14 | §§ | §§ | §§
… | All causes | 45 | 100.0 | 27.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 11 | 24.4 | 6.6
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
4 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
6 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
6 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
6 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
… | All other causes(residual) | 13 | 28.9 | 7.8
| American Indian and Alaska Native, non-Hispanic, both sexes, 15–19
… | All causes | 189 | 100.0 | 104.8
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 79 | 41.8 | 43.8
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 47 | 24.9 | 26.1
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 30 | 15.9 | 16.6
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
5 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
7 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
7 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
7 | Pregnancy, childbirth and the puerperium(O00–O99) | §§ | §§ | §§
7 | Complications of medical and surgical care(Y40–Y84,Y88) | §§ | §§ | §§
7 | Pneumonitis due to solids and liquids(J69) | §§ | §§ | §§
… | All other causes(residual) | 18 | 9.5 | 10.0
| American Indian and Alaska Native, non-Hispanic, both sexes, 20–24
… | All causes | 354 | 100.0 | 200.4
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 167 | 47.2 | 94.6
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 73 | 20.6 | 41.3
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 37 | 10.5 | 20.9
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
5 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
7 | Septicemia(A40–A41) | §§ | §§ | §§
7 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
7 | Pregnancy, childbirth and the puerperium(O00–O99) | §§ | §§ | §§
7 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
… | All other causes(residual) | 43 | 12.1 | 24.3
| American Indian and Alaska Native, non-Hispanic, both sexes, 25–34
… | All causes | 1,284 | 100.0 | 347.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 501 | 39.0 | 135.5
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 155 | 12.1 | 41.9
2 | Chronic liver disease and cirrhosis(K70,K73–K74) | 155 | 12.1 | 41.9
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 94 | 7.3 | 25.4
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 54 | 4.2 | 14.6
6 | Malignant neoplasms(C00–C97) | 30 | 2.3 | 8.1
7 | Diabetes mellitus(E10–E14) | 27 | 2.1 | 7.3
8 | Influenza and pneumonia(J09–J18) | 19 | 1.5 | 5.1
9 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 224 | 17.4 | 60.6
| American Indian and Alaska Native, non-Hispanic, both sexes, 35–44
… | All causes | 1,855 | 100.0 | 566.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 596 | 32.1 | 181.9
2 | Chronic liver disease and cirrhosis(K70,K73–K74) | 261 | 14.1 | 79.7
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 170 | 9.2 | 51.9
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 124 | 6.7 | 37.8
5 | Malignant neoplasms(C00–C97) | 84 | 4.5 | 25.6
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 65 | 3.5 | 19.8
7 | Diabetes mellitus(E10–E14) | 64 | 3.5 | 19.5
8 | Influenza and pneumonia(J09–J18) | 32 | 1.7 | 9.8
9 | Septicemia(A40–A41) | 28 | 1.5 | 8.5
10 | Cerebrovascular diseases(I60–I69) | 26 | 1.4 | 7.9
… | All other causes(residual) | 405 | 21.8 | 123.6
| American Indian and Alaska Native, non-Hispanic, both sexes, 45–54
… | All causes | 2,221 | 100.0 | 800.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 419 | 18.9 | 151.1
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 326 | 14.7 | 117.6
3 | Chronic liver disease and cirrhosis(K70,K73–K74) | 312 | 14.0 | 112.5
4 | Malignant neoplasms(C00–C97) | 241 | 10.9 | 86.9
5 | Diabetes mellitus(E10–E14) | 130 | 5.9 | 46.9
6 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 72 | 3.2 | 26.0
7 | Cerebrovascular diseases(I60–I69) | 51 | 2.3 | 18.4
7 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 51 | 2.3 | 18.4
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 42 | 1.9 | 15.1
9 | Septicemia(A40–A41) | 42 | 1.9 | 15.1
… | All other causes(residual) | 535 | 24.1 | 192.9
| American Indian and Alaska Native, non-Hispanic, both sexes, 55–64
… | All causes | 3,534 | 100.0 | 1,227.4
1 | Malignant neoplasms(C00–C97) | 691 | 19.6 | 240.0
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 645 | 18.3 | 224.0
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 415 | 11.7 | 144.1
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 295 | 8.3 | 102.5
5 | Diabetes mellitus(E10–E14) | 228 | 6.5 | 79.2
6 | Chronic lower respiratory diseases(J40–J47) | 118 | 3.3 | 41.0
7 | Cerebrovascular diseases(I60–I69) | 116 | 3.3 | 40.3
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 71 | 2.0 | 24.7
9 | Septicemia(A40–A41) | 61 | 1.7 | 21.2
10 | Influenza and pneumonia(J09–J18) | 60 | 1.7 | 20.8
… | All other causes(residual) | 834 | 23.6 | 289.7
| American Indian and Alaska Native, non-Hispanic, both sexes, 65 and older
… | All causes | 11,143 | 100.0 | 2,900.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 2,479 | 22.2 | 645.3
2 | Malignant neoplasms(C00–C97) | 2,165 | 19.4 | 563.5
3 | Chronic lower respiratory diseases(J40–J47) | 665 | 6.0 | 173.1
4 | Diabetes mellitus(E10–E14) | 651 | 5.8 | 169.4
5 | Cerebrovascular diseases(I60–I69) | 577 | 5.2 | 150.2
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 457 | 4.1 | 119.0
7 | Alzheimer disease(G30) | 358 | 3.2 | 93.2
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | 256 | 2.3 | 66.6
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 244 | 2.2 | 63.5
10 | Influenza and pneumonia(J09–J18) | 196 | 1.8 | 51.0
… | All other causes(residual) | 3,095 | 27.8 | 805.6
| American Indian and Alaska Native, non-Hispanic, both sexes, 65–74
… | All causes | 4,519 | 100.0 | 1,952.3
1 | Malignant neoplasms(C00–C97) | 1,052 | 23.3 | 454.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 912 | 20.2 | 394.0
3 | Diabetes mellitus(E10–E14) | 339 | 7.5 | 146.5
4 | Chronic lower respiratory diseases(J40–J47) | 296 | 6.6 | 127.9
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 241 | 5.3 | 104.1
6 | Cerebrovascular diseases(I60–I69) | 201 | 4.4 | 86.8
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 181 | 4.0 | 78.2
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 106 | 2.3 | 45.8
9 | Influenza and pneumonia(J09–J18) | 71 | 1.6 | 30.7
10 | Septicemia(A40–A41) | 68 | 1.5 | 29.4
… | All other causes(residual) | 1,052 | 23.3 | 454.5
| American Indian and Alaska Native, non-Hispanic, both sexes, 75–84
… | All causes | 3,981 | 100.0 | 3,482.6
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 918 | 23.1 | 803.1
2 | Malignant neoplasms(C00–C97) | 794 | 19.9 | 694.6
3 | Chronic lower respiratory diseases(J40–J47) | 237 | 6.0 | 207.3
4 | Diabetes mellitus(E10–E14) | 215 | 5.4 | 188.1
5 | Cerebrovascular diseases(I60–I69) | 208 | 5.2 | 182.0
6 | Alzheimer disease(G30) | 141 | 3.5 | 123.3
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 119 | 3.0 | 104.1
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 87 | 2.2 | 76.1
9 | Septicemia(A40–A41) | 72 | 1.8 | 63.0
10 | Influenza and pneumonia(J09–J18) | 71 | 1.8 | 62.1
… | All other causes(residual) | 1,119 | 28.1 | 978.9
| American Indian and Alaska Native, non-Hispanic, both sexes, 85 and older
… | All causes | 2,643 | 100.0 | 6,881.2
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 649 | 24.6 | 1,689.7
2 | Malignant neoplasms(C00–C97) | 319 | 12.1 | 830.5
3 | Alzheimer disease(G30) | 178 | 6.7 | 463.4
4 | Cerebrovascular diseases(I60–I69) | 168 | 6.4 | 437.4
5 | Chronic lower respiratory diseases(J40–J47) | 132 | 5.0 | 343.7
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 97 | 3.7 | 252.5
6 | Diabetes mellitus(E10–E14) | 97 | 3.7 | 252.5
8 | Influenza and pneumonia(J09–J18) | 54 | 2.0 | 140.6
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 51 | 1.9 | 132.8
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 50 | 1.9 | 130.2
… | All other causes(residual) | 848 | 32.1 | 2,207.8
| American Indian and Alaska Native, non-Hispanic, male, all ages^††^
… | All causes | 11,356 | 100.0 | 943.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 2,147 | 18.9 | 178.4
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,722 | 15.2 | 143.0
3 | Malignant neoplasms(C00–C97) | 1,643 | 14.5 | 136.5
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 679 | 6.0 | 56.4
5 | Diabetes mellitus(E10–E14) | 584 | 5.1 | 48.5
6 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 419 | 3.7 | 34.8
7 | Cerebrovascular diseases(I60–I69) | 375 | 3.3 | 31.2
8 | Chronic lower respiratory diseases(J40–J47) | 372 | 3.3 | 30.9
9 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 255 | 2.2 | 21.2
10 | Influenza and pneumonia(J09–J18) | 199 | 1.8 | 16.5
… | All other causes(residual) | 2,961 | 26.1 | 246.0
| American Indian and Alaska Native, non-Hispanic, male, 1–4
… | All causes | 27 | 100.0 | 53.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 13 | 48.1 | 25.7
2 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
4 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| American Indian and Alaska Native, non-Hispanic, male, 5–9
… | All causes | 18 | 100.0 | 23.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
3 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
4 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| American Indian and Alaska Native, non-Hispanic, male, 10–14
… | All causes | 31 | 100.0 | 36.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
5 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
5 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
… | All other causes(residual) | 10 | 32.3 | 11.8
| American Indian and Alaska Native, non-Hispanic, male, 15–19
… | All causes | 127 | 100.0 | 138.8
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 47 | 37.0 | 51.4
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 34 | 26.8 | 37.2
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 25 | 19.7 | 27.3
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
6 | Pneumonitis due to solids and liquids(J69) | §§ | §§ | §§
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
6 | Complications of medical and surgical care(Y40–Y84,Y88) | §§ | §§ | §§
6 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
… | All other causes(residual) | 11 | 8.7 | 12.0
| American Indian and Alaska Native, non-Hispanic, male, 20–24
… | All causes | 243 | 100.0 | 271.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 100 | 41.2 | 111.6
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 60 | 24.7 | 66.9
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 34 | 14.0 | 37.9
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
6 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
7 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
7 | Legal intervention(Y35,Y89.0) | §§ | §§ | §§
7 | Septicemia(A40–A41) | §§ | §§ | §§
10 | Anemias(D50–D64) | §§ | §§ | §§
10 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
10 | Diseases of appendix(K35–K38) | §§ | §§ | §§
… | All other causes(residual) | 24 | 9.9 | 26.8
| American Indian and Alaska Native, non-Hispanic, male, 25–34
… | All causes | 839 | 100.0 | 449.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 321 | 38.3 | 171.8
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 126 | 15.0 | 67.4
3 | Chronic liver disease and cirrhosis(K70,K73–K74) | 78 | 9.3 | 41.7
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 77 | 9.2 | 41.2
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 42 | 5.0 | 22.5
6 | Malignant neoplasms(C00–C97) | 16 | 1.9 | 8.6
7 | Diabetes mellitus(E10–E14) | 15 | 1.8 | 8.0
8 | Influenza and pneumonia(J09–J18) | 12 | 1.4 | 6.4
9 | Septicemia(A40–A41) | §§ | §§ | §§
9 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
… | All other causes(residual) | 142 | 16.9 | 76.0
| American Indian and Alaska Native, non-Hispanic, male, 35–44
… | All causes | 1,133 | 100.0 | 692.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 382 | 33.7 | 233.3
2 | Chronic liver disease and cirrhosis(K70,K73–K74) | 147 | 13.0 | 89.8
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 111 | 9.8 | 67.8
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 87 | 7.7 | 53.1
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 43 | 3.8 | 26.3
6 | Malignant neoplasms(C00–C97) | 35 | 3.1 | 21.4
7 | Diabetes mellitus(E10–E14) | 34 | 3.0 | 20.8
8 | Cerebrovascular diseases(I60–I69) | 19 | 1.7 | 11.6
8 | Influenza and pneumonia(J09–J18) | 19 | 1.7 | 11.6
10 | Septicemia(A40–A41) | 17 | 1.5 | 10.4
… | All other causes(residual) | 239 | 21.1 | 146.0
| American Indian and Alaska Native, non-Hispanic, male, 45–54
… | All causes | 1,359 | 100.0 | 995.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 283 | 20.8 | 207.2
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 226 | 16.6 | 165.5
3 | Chronic liver disease and cirrhosis(K70,K73–K74) | 181 | 13.3 | 132.5
4 | Malignant neoplasms(C00–C97) | 113 | 8.3 | 82.7
5 | Diabetes mellitus(E10–E14) | 70 | 5.2 | 51.3
6 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 56 | 4.1 | 41.0
7 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 39 | 2.9 | 28.6
8 | Cerebrovascular diseases(I60–I69) | 32 | 2.4 | 23.4
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 25 | 1.8 | 18.3
10 | Influenza and pneumonia(J09–J18) | 23 | 1.7 | 16.8
… | All other causes(residual) | 311 | 22.9 | 227.7
| American Indian and Alaska Native, non-Hispanic, male, 55–64
… | All causes | 2,086 | 100.0 | 1,511.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 436 | 20.9 | 315.9
2 | Malignant neoplasms(C00–C97) | 371 | 17.8 | 268.8
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 303 | 14.5 | 219.5
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 144 | 6.9 | 104.3
5 | Diabetes mellitus(E10–E14) | 133 | 6.4 | 96.4
6 | Cerebrovascular diseases(I60–I69) | 60 | 2.9 | 43.5
7 | Chronic lower respiratory diseases(J40–J47) | 59 | 2.8 | 42.7
8 | Influenza and pneumonia(J09–J18) | 35 | 1.7 | 25.4
9 | Septicemia(A40–A41) | 31 | 1.5 | 22.5
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 31 | 1.5 | 22.5
… | All other causes(residual) | 483 | 23.2 | 350.0
| American Indian and Alaska Native, non-Hispanic, male, 65 and older
… | All causes | 5,364 | 100.0 | 3,086.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,322 | 24.6 | 760.7
2 | Malignant neoplasms(C00–C97) | 1,097 | 20.5 | 631.3
3 | Diabetes mellitus(E10–E14) | 331 | 6.2 | 190.5
4 | Chronic lower respiratory diseases(J40–J47) | 289 | 5.4 | 166.3
5 | Cerebrovascular diseases(I60–I69) | 259 | 4.8 | 149.0
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 243 | 4.5 | 139.8
7 | Alzheimer disease(G30) | 125 | 2.3 | 71.9
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | 122 | 2.3 | 70.2
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 109 | 2.0 | 62.7
10 | Influenza and pneumonia(J09–J18) | 105 | 2.0 | 60.4
… | All other causes(residual) | 1,362 | 25.4 | 783.7
| American Indian and Alaska Native, non-Hispanic, male, 65–74
… | All causes | 2,459 | 100.0 | 2,307.3
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 580 | 23.6 | 544.2
2 | Malignant neoplasms(C00–C97) | 566 | 23.0 | 531.1
3 | Diabetes mellitus(E10–E14) | 183 | 7.4 | 171.7
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 141 | 5.7 | 132.3
5 | Chronic lower respiratory diseases(J40–J47) | 131 | 5.3 | 122.9
6 | Cerebrovascular diseases(I60–I69) | 112 | 4.6 | 105.1
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 88 | 3.6 | 82.6
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 52 | 2.1 | 48.8
9 | Influenza and pneumonia(J09–J18) | 40 | 1.6 | 37.5
10 | Septicemia(A40–A41) | 30 | 1.2 | 28.1
… | All other causes(residual) | 536 | 21.8 | 502.9
| American Indian and Alaska Native, non-Hispanic, male, 75–84
… | All causes | 1,900 | 100.0 | 3,666.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 473 | 24.9 | 912.8
2 | Malignant neoplasms(C00–C97) | 397 | 20.9 | 766.1
3 | Diabetes mellitus(E10–E14) | 111 | 5.8 | 214.2
4 | Chronic lower respiratory diseases(J40–J47) | 101 | 5.3 | 194.9
5 | Cerebrovascular diseases(I60–I69) | 90 | 4.7 | 173.7
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 62 | 3.3 | 119.6
7 | Alzheimer disease(G30) | 56 | 2.9 | 108.1
8 | Influenza and pneumonia(J09–J18) | 43 | 2.3 | 83.0
9 | Septicemia(A40–A41) | 41 | 2.2 | 79.1
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 35 | 1.8 | 67.5
… | All other causes(residual) | 491 | 25.8 | 947.5
| American Indian and Alaska Native, non-Hispanic, male, 85 and older
… | All causes | 1,005 | 100.0 | 6,531.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 269 | 26.8 | 1,748.2
2 | Malignant neoplasms(C00–C97) | 134 | 13.3 | 870.9
3 | Cerebrovascular diseases(I60–I69) | 57 | 5.7 | 370.4
3 | Chronic lower respiratory diseases(J40–J47) | 57 | 5.7 | 370.4
5 | Alzheimer disease(G30) | 53 | 5.3 | 344.4
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 40 | 4.0 | 260.0
7 | Diabetes mellitus(E10–E14) | 37 | 3.7 | 240.5
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 22 | 2.2 | 143.0
8 | Influenza and pneumonia(J09–J18) | 22 | 2.2 | 143.0
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 22 | 2.2 | 143.0
… | All other causes(residual) | 292 | 29.1 | 1,897.7
| American Indian and Alaska Native, non-Hispanic, female, all ages^††^
… | All causes | 9,568 | 100.0 | 772.5
1 | Malignant neoplasms(C00–C97) | 1,586 | 16.6 | 128.0
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,541 | 16.1 | 124.4
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 982 | 10.3 | 79.3
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 608 | 6.4 | 49.1
5 | Diabetes mellitus(E10–E14) | 520 | 5.4 | 42.0
6 | Chronic lower respiratory diseases(J40–J47) | 457 | 4.8 | 36.9
7 | Cerebrovascular diseases(I60–I69) | 407 | 4.3 | 32.9
8 | Alzheimer disease(G30) | 237 | 2.5 | 19.1
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 205 | 2.1 | 16.6
10 | Influenza and pneumonia(J09–J18) | 157 | 1.6 | 12.7
… | All other causes(residual) | 2,868 | 30.0 | 231.5
| American Indian and Alaska Native, non-Hispanic, female, 1–4
… | All causes | 25 | 100.0 | 51.4
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
3 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
3 | Septicemia(A40–A41) | §§ | §§ | §§
3 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
… | All other causes(residual) | 10 | 40.0 | 20.6
| American Indian and Alaska Native, non-Hispanic, female, 5–9
… | All causes | 20 | 100.0 | 27.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
3 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
3 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
3 | Certain conditions originating in the perinatal period(P00–P96) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| American Indian and Alaska Native, non-Hispanic, female, 10–14
… | All causes | 14 | 100.0 | 17.2
1 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
2 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
4 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
4 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| American Indian and Alaska Native, non-Hispanic, female, 15–19
… | All causes | 62 | 100.0 | 69.8
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 32 | 51.6 | 36.0
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 13 | 21.0 | 14.6
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
4 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
4 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
4 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Pregnancy, childbirth and the puerperium(O00–O99) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| American Indian and Alaska Native, non-Hispanic, female, 20–24
… | All causes | 111 | 100.0 | 127.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 67 | 60.4 | 77.0
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 13 | 11.7 | 14.9
3 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
3 | Pregnancy, childbirth and the puerperium(O00–O99) | §§ | §§ | §§
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
6 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
6 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
9 | Septicemia(A40–A41) | §§ | §§ | §§
9 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
9 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
9 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 11 | 9.9 | 12.6
| American Indian and Alaska Native, non-Hispanic, female, 25–34
… | All causes | 445 | 100.0 | 243.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 180 | 40.4 | 98.4
2 | Chronic liver disease and cirrhosis(K70,K73–K74) | 77 | 17.3 | 42.1
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 29 | 6.5 | 15.8
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 17 | 3.8 | 9.3
5 | Malignant neoplasms(C00–C97) | 14 | 3.1 | 7.7
6 | Diabetes mellitus(E10–E14) | 12 | 2.7 | 6.6
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 12 | 2.7 | 6.6
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
9 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
… | All other causes(residual) | 87 | 19.6 | 47.5
| American Indian and Alaska Native, non-Hispanic, female, 35–44
… | All causes | 722 | 100.0 | 440.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 214 | 29.6 | 130.5
2 | Chronic liver disease and cirrhosis(K70,K73–K74) | 114 | 15.8 | 69.5
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 59 | 8.2 | 36.0
4 | Malignant neoplasms(C00–C97) | 49 | 6.8 | 29.9
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 37 | 5.1 | 22.6
6 | Diabetes mellitus(E10–E14) | 30 | 4.2 | 18.3
7 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 22 | 3.0 | 13.4
8 | Influenza and pneumonia(J09–J18) | 13 | 1.8 | 7.9
9 | Septicemia(A40–A41) | 11 | 1.5 | 6.7
10 | Pregnancy, childbirth and the puerperium(O00–O99) | §§ | §§ | §§
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
10 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
… | All other causes(residual) | 152 | 21.1 | 92.7
| American Indian and Alaska Native, non-Hispanic, female, 45–54
… | All causes | 862 | 100.0 | 612.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 136 | 15.8 | 96.6
2 | Chronic liver disease and cirrhosis(K70,K73–K74) | 131 | 15.2 | 93.1
3 | Malignant neoplasms(C00–C97) | 128 | 14.8 | 91.0
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 100 | 11.6 | 71.1
5 | Diabetes mellitus(E10–E14) | 60 | 7.0 | 42.6
6 | Septicemia(A40–A41) | 22 | 2.6 | 15.6
7 | Cerebrovascular diseases(I60–I69) | 19 | 2.2 | 13.5
8 | Influenza and pneumonia(J09–J18) | 17 | 2.0 | 12.1
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 17 | 2.0 | 12.1
10 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 16 | 1.9 | 11.4
… | All other causes(residual) | 216 | 25.1 | 153.5
| American Indian and Alaska Native, non-Hispanic, female, 55–64
… | All causes | 1,448 | 100.0 | 965.9
1 | Malignant neoplasms(C00–C97) | 320 | 22.1 | 213.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 209 | 14.4 | 139.4
3 | Chronic liver disease and cirrhosis(K70,K73–K74) | 151 | 10.4 | 100.7
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 112 | 7.7 | 74.7
5 | Diabetes mellitus(E10–E14) | 95 | 6.6 | 63.4
6 | Chronic lower respiratory diseases(J40–J47) | 59 | 4.1 | 39.4
7 | Cerebrovascular diseases(I60–I69) | 56 | 3.9 | 37.4
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 40 | 2.8 | 26.7
9 | Septicemia(A40–A41) | 30 | 2.1 | 20.0
10 | Influenza and pneumonia(J09–J18) | 25 | 1.7 | 16.7
… | All other causes(residual) | 351 | 24.2 | 234.1
| American Indian and Alaska Native, non-Hispanic, female, 65 and older
… | All causes | 5,779 | 100.0 | 2,746.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,157 | 20.0 | 549.9
2 | Malignant neoplasms(C00–C97) | 1,068 | 18.5 | 507.6
3 | Chronic lower respiratory diseases(J40–J47) | 376 | 6.5 | 178.7
4 | Diabetes mellitus(E10–E14) | 320 | 5.5 | 152.1
5 | Cerebrovascular diseases(I60–I69) | 318 | 5.5 | 151.1
6 | Alzheimer disease(G30) | 233 | 4.0 | 110.7
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 214 | 3.7 | 101.7
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 135 | 2.3 | 64.2
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | 134 | 2.3 | 63.7
10 | Influenza and pneumonia(J09–J18) | 91 | 1.6 | 43.2
… | All other causes(residual) | 1,733 | 30.0 | 823.6
| American Indian and Alaska Native, non-Hispanic, female, 65–74
… | All causes | 2,060 | 100.0 | 1,649.3
1 | Malignant neoplasms(C00–C97) | 486 | 23.6 | 389.1
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 332 | 16.1 | 265.8
3 | Chronic lower respiratory diseases(J40–J47) | 165 | 8.0 | 132.1
4 | Diabetes mellitus(E10–E14) | 156 | 7.6 | 124.9
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 100 | 4.9 | 80.1
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 93 | 4.5 | 74.5
7 | Cerebrovascular diseases(I60–I69) | 89 | 4.3 | 71.3
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 54 | 2.6 | 43.2
9 | Septicemia(A40–A41) | 38 | 1.8 | 30.4
10 | Influenza and pneumonia(J09–J18) | 31 | 1.5 | 24.8
… | All other causes(residual) | 516 | 25.0 | 413.1
| American Indian and Alaska Native, non-Hispanic, female, 75–84
… | All causes | 2,081 | 100.0 | 3,330.1
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 445 | 21.4 | 712.1
2 | Malignant neoplasms(C00–C97) | 397 | 19.1 | 635.3
3 | Chronic lower respiratory diseases(J40–J47) | 136 | 6.5 | 217.6
4 | Cerebrovascular diseases(I60–I69) | 118 | 5.7 | 188.8
5 | Diabetes mellitus(E10–E14) | 104 | 5.0 | 166.4
6 | Alzheimer disease(G30) | 85 | 4.1 | 136.0
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 57 | 2.7 | 91.2
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 52 | 2.5 | 83.2
9 | Septicemia(A40–A41) | 31 | 1.5 | 49.6
10 | Chronic liver disease and cirrhosis(K70,K73–K74) | 30 | 1.4 | 48.0
… | All other causes(residual) | 626 | 30.1 | 1,001.7
| American Indian and Alaska Native, non-Hispanic, female, 85 and older
… | All causes | 1,638 | 100.0 | 7,114.9
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 380 | 23.2 | 1,650.6
2 | Malignant neoplasms(C00–C97) | 185 | 11.3 | 803.6
3 | Alzheimer disease(G30) | 125 | 7.6 | 543.0
4 | Cerebrovascular diseases(I60–I69) | 111 | 6.8 | 482.1
5 | Chronic lower respiratory diseases(J40–J47) | 75 | 4.6 | 325.8
6 | Diabetes mellitus(E10–E14) | 60 | 3.7 | 260.6
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 57 | 3.5 | 247.6
8 | Influenza and pneumonia(J09–J18) | 32 | 2.0 | 139.0
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 29 | 1.8 | 126.0
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 28 | 1.7 | 121.6
… | All other causes(residual) | 556 | 33.9 | 2,415.1
| Asian, non-Hispanic, both sexes, all ages^††^
… | All causes | 87,728 | 100.0 | 397.3
1 | Malignant neoplasms(C00–C97) | 20,575 | 23.5 | 93.2
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 17,742 | 20.2 | 80.4
3 | Cerebrovascular diseases(I60–I69) | 6,662 | 7.6 | 30.2
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,228 | 4.8 | 19.1
5 | Diabetes mellitus(E10–E14) | 3,865 | 4.4 | 17.5
6 | Alzheimer disease(G30) | 3,425 | 3.9 | 15.5
7 | Influenza and pneumonia(J09–J18) | 2,026 | 2.3 | 9.2
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,961 | 2.2 | 8.9
9 | Chronic lower respiratory diseases(J40–J47) | 1,843 | 2.1 | 8.3
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,830 | 2.1 | 8.3
… | All other causes(residual) | 23,571 | 26.9 | 106.7
| Asian, non-Hispanic, both sexes, 1–4
… | All causes | 137 | 100.0 | 15.4
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 42 | 30.7 | 4.7
2 | Malignant neoplasms(C00–C97) | 15 | 10.9 | 1.7
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 11 | 8.0 | 1.2
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
5 | Septicemia(A40–A41) | §§ | §§ | §§
6 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
8 | Certain conditions originating in the perinatal period(P00–P96) | §§ | §§ | §§
9 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
9 | Anemias(D50–D64) | §§ | §§ | §§
9 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
9 | Pneumonitis due to solids and liquids(J69) | §§ | §§ | §§
9 | Complications of medical and surgical care(Y40–Y84,Y88) | §§ | §§ | §§
9 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
9 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 34 | 24.8 | 3.8
| Asian, non-Hispanic, both sexes, 5–9
… | All causes | 113 | 100.0 | 9.1
1 | Malignant neoplasms(C00–C97) | 29 | 25.7 | 2.3
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 27 | 23.9 | 2.2
3 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
7 | Septicemia(A40–A41) | §§ | §§ | §§
7 | Anemias(D50–D64) | §§ | §§ | §§
7 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
10 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
10 | Meningococcal infection(A39) | §§ | §§ | §§
10 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 29 | 25.7 | 2.3
| Asian, non-Hispanic, both sexes, 10–14
… | All causes | 122 | 100.0 | 10.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 25 | 20.5 | 2.1
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 19 | 15.6 | 1.6
3 | Malignant neoplasms(C00–C97) | 16 | 13.1 | 1.3
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
5 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
7 | Complications of medical and surgical care(Y40–Y84,Y88) | §§ | §§ | §§
7 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
7 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
7 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
… | All other causes(residual) | 37 | 30.3 | 3.0
| Asian, non-Hispanic, both sexes, 15–19
… | All causes | 292 | 100.0 | 23.5
1 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 90 | 30.8 | 7.2
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 89 | 30.5 | 7.2
3 | Malignant neoplasms(C00–C97) | 30 | 10.3 | 2.4
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 16 | 5.5 | 1.3
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 11 | 3.8 | 0.9
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
7 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
7 | Legal intervention(Y35,Y89.0) | §§ | §§ | §§
7 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
10 | Complications of medical and surgical care(Y40–Y84,Y88) | §§ | §§ | §§
10 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
… | All other causes(residual) | 32 | 11.0 | 2.6
| Asian, non-Hispanic, both sexes, 20–24
… | All causes | 510 | 100.0 | 35.2
1 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 195 | 38.2 | 13.5
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 158 | 31.0 | 10.9
3 | Malignant neoplasms(C00–C97) | 43 | 8.4 | 3.0
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 17 | 3.3 | 1.2
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 16 | 3.1 | 1.1
6 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
7 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
8 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
… | All other causes(residual) | 63 | 12.4 | 4.4
| Asian, non-Hispanic, both sexes, 25–34
… | All causes | 1,426 | 100.0 | 40.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 387 | 27.1 | 11.0
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 317 | 22.2 | 9.0
3 | Malignant neoplasms(C00–C97) | 167 | 11.7 | 4.8
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 102 | 7.2 | 2.9
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 56 | 3.9 | 1.6
6 | Cerebrovascular diseases(I60–I69) | 39 | 2.7 | 1.1
7 | Pregnancy, childbirth and the puerperium(O00–O99) | 33 | 2.3 | 0.9
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | 25 | 1.8 | 0.7
9 | Diabetes mellitus(E10–E14) | 21 | 1.5 | 0.6
10 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 16 | 1.1 | 0.5
… | All other causes(residual) | 263 | 18.4 | 7.5
| Asian, non-Hispanic, both sexes, 35–44
… | All causes | 2,472 | 100.0 | 67.2
1 | Malignant neoplasms(C00–C97) | 567 | 22.9 | 15.4
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 475 | 19.2 | 12.9
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 322 | 13.0 | 8.8
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 240 | 9.7 | 6.5
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 115 | 4.7 | 3.1
6 | Cerebrovascular diseases(I60–I69) | 104 | 4.2 | 2.8
7 | Diabetes mellitus(E10–E14) | 78 | 3.2 | 2.1
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 57 | 2.3 | 1.6
9 | Influenza and pneumonia(J09–J18) | 26 | 1.1 | 0.7
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 21 | 0.8 | 0.6
… | All other causes(residual) | 467 | 18.9 | 12.7
| Asian, non-Hispanic, both sexes, 45–54
… | All causes | 4,627 | 100.0 | 152.3
1 | Malignant neoplasms(C00–C97) | 1,518 | 32.8 | 50.0
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 820 | 17.7 | 27.0
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 451 | 9.7 | 14.8
4 | Cerebrovascular diseases(I60–I69) | 312 | 6.7 | 10.3
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 223 | 4.8 | 7.3
6 | Diabetes mellitus(E10–E14) | 196 | 4.2 | 6.5
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 136 | 2.9 | 4.5
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 74 | 1.6 | 2.4
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 59 | 1.3 | 1.9
10 | Influenza and pneumonia(J09–J18) | 48 | 1.0 | 1.6
… | All other causes(residual) | 790 | 17.1 | 26.0
| Asian, non-Hispanic, both sexes, 55–64
… | All causes | 8,465 | 100.0 | 348.9
1 | Malignant neoplasms(C00–C97) | 3,313 | 39.1 | 136.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,626 | 19.2 | 67.0
3 | Cerebrovascular diseases(I60–I69) | 505 | 6.0 | 20.8
4 | Diabetes mellitus(E10–E14) | 404 | 4.8 | 16.6
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 394 | 4.7 | 16.2
6 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 200 | 2.4 | 8.2
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 196 | 2.3 | 8.1
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 160 | 1.9 | 6.6
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 118 | 1.4 | 4.9
10 | Influenza and pneumonia(J09–J18) | 113 | 1.3 | 4.7
… | All other causes(residual) | 1,436 | 17.0 | 59.2
| Asian, non-Hispanic, both sexes, 65 and older
… | All causes | 68,880 | 100.0 | 2,157.1
1 | Malignant neoplasms(C00–C97) | 14,875 | 21.6 | 465.8
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 14,817 | 21.5 | 464.0
3 | Cerebrovascular diseases(I60–I69) | 5,685 | 8.3 | 178.0
4 | Alzheimer disease(G30) | 3,405 | 4.9 | 106.6
5 | Diabetes mellitus(E10–E14) | 3,163 | 4.6 | 99.1
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 2,166 | 3.1 | 67.8
7 | Influenza and pneumonia(J09–J18) | 1,805 | 2.6 | 56.5
8 | Chronic lower respiratory diseases(J40–J47) | 1,711 | 2.5 | 53.6
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,693 | 2.5 | 53.0
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,630 | 2.4 | 51.0
… | All other causes(residual) | 17,930 | 26.0 | 561.5
| Asian, non-Hispanic, both sexes, 65–74
… | All causes | 15,311 | 100.0 | 823.0
1 | Malignant neoplasms(C00–C97) | 5,351 | 34.9 | 287.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 2,991 | 19.5 | 160.8
3 | Cerebrovascular diseases(I60–I69) | 995 | 6.5 | 53.5
4 | Diabetes mellitus(E10–E14) | 839 | 5.5 | 45.1
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 496 | 3.2 | 26.7
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 368 | 2.4 | 19.8
7 | Influenza and pneumonia(J09–J18) | 293 | 1.9 | 15.8
8 | Chronic lower respiratory diseases(J40–J47) | 288 | 1.9 | 15.5
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 253 | 1.7 | 13.6
10 | Parkinson disease(G20–G21) | 197 | 1.3 | 10.6
… | All other causes(residual) | 3,240 | 21.2 | 174.2
| Asian, non-Hispanic, both sexes, 75–84
… | All causes | 22,722 | 100.0 | 2,350.0
1 | Malignant neoplasms(C00–C97) | 5,645 | 24.8 | 583.8
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 4,616 | 20.3 | 477.4
3 | Cerebrovascular diseases(I60–I69) | 1,756 | 7.7 | 181.6
4 | Diabetes mellitus(E10–E14) | 1,203 | 5.3 | 124.4
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 762 | 3.4 | 78.8
6 | Alzheimer disease(G30) | 737 | 3.2 | 76.2
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 593 | 2.6 | 61.3
8 | Chronic lower respiratory diseases(J40–J47) | 588 | 2.6 | 60.8
9 | Influenza and pneumonia(J09–J18) | 577 | 2.5 | 59.7
10 | Parkinson disease(G20–G21) | 559 | 2.5 | 57.8
… | All other causes(residual) | 5,686 | 25.0 | 588.1
| Asian, non-Hispanic, both sexes, 85 and older
… | All causes | 30,847 | 100.0 | 8,428.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 7,210 | 23.4 | 1,970.1
2 | Malignant neoplasms(C00–C97) | 3,879 | 12.6 | 1,059.9
3 | Cerebrovascular diseases(I60–I69) | 2,934 | 9.5 | 801.7
4 | Alzheimer disease(G30) | 2,505 | 8.1 | 684.5
5 | Diabetes mellitus(E10–E14) | 1,121 | 3.6 | 306.3
6 | Influenza and pneumonia(J09–J18) | 935 | 3.0 | 255.5
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 908 | 2.9 | 248.1
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 892 | 2.9 | 243.7
9 | Chronic lower respiratory diseases(J40–J47) | 835 | 2.7 | 228.2
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 732 | 2.4 | 200.0
… | All other causes(residual) | 8,896 | 28.8 | 2,430.8
| Asian, non-Hispanic, male, all ages^††^
… | All causes | 45,118 | 100.0 | 425.3
1 | Malignant neoplasms(C00–C97) | 10,217 | 22.6 | 96.3
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 9,915 | 22.0 | 93.5
3 | Cerebrovascular diseases(I60–I69) | 3,020 | 6.7 | 28.5
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 2,741 | 6.1 | 25.8
5 | Diabetes mellitus(E10–E14) | 2,090 | 4.6 | 19.7
6 | Influenza and pneumonia(J09–J18) | 1,136 | 2.5 | 10.7
7 | Chronic lower respiratory diseases(J40–J47) | 1,110 | 2.5 | 10.5
8 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,069 | 2.4 | 10.1
9 | Alzheimer disease(G30) | 1,066 | 2.4 | 10.0
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,044 | 2.3 | 9.8
… | All other causes(residual) | 11,710 | 26.0 | 110.4
| Asian, non-Hispanic, male, 1–4
… | All causes | 76 | 100.0 | 16.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 25 | 32.9 | 5.5
2 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Septicemia(A40–A41) | §§ | §§ | §§
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
6 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
7 | Certain conditions originating in the perinatal period(P00–P96) | §§ | §§ | §§
7 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
9 | Anemias(D50–D64) | §§ | §§ | §§
9 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
9 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
9 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
9 | Pneumonitis due to solids and liquids(J69) | §§ | §§ | §§
… | All other causes(residual) | 20 | 26.3 | 4.4
| Asian, non-Hispanic, male, 5–9
… | All causes | 68 | 100.0 | 10.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 20 | 29.4 | 3.1
1 | Malignant neoplasms(C00–C97) | 20 | 29.4 | 3.1
3 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
4 | Septicemia(A40–A41) | §§ | §§ | §§
4 | Anemias(D50–D64) | §§ | §§ | §§
8 | Meningococcal infection(A39) | §§ | §§ | §§
8 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
8 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 11 | 16.2 | 1.7
| Asian, non-Hispanic, male, 10–14
… | All causes | 76 | 100.0 | 12.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 17 | 22.4 | 2.7
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 11 | 14.5 | 1.8
3 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
4 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
5 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
8 | Aortic aneurysm and dissection(I71) | §§ | §§ | §§
8 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
8 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
… | All other causes(residual) | 21 | 27.6 | 3.4
| Asian, non-Hispanic, male, 15–19
… | All causes | 177 | 100.0 | 27.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 65 | 36.7 | 10.3
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 48 | 27.1 | 7.6
3 | Malignant neoplasms(C00–C97) | 16 | 9.0 | 2.5
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 10 | 5.6 | 1.6
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
7 | Legal intervention(Y35,Y89.0) | §§ | §§ | §§
8 | Septicemia(A40–A41) | §§ | §§ | §§
8 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
10 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
10 | Aortic aneurysm and dissection(I71) | §§ | §§ | §§
… | All other causes(residual) | 15 | 8.5 | 2.4
| Asian, non-Hispanic, male, 20–24
… | All causes | 361 | 100.0 | 49.4
1 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 139 | 38.5 | 19.0
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 124 | 34.3 | 17.0
3 | Malignant neoplasms(C00–C97) | 28 | 7.8 | 3.8
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 13 | 3.6 | 1.8
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 11 | 3.0 | 1.5
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
7 | Legal intervention(Y35,Y89.0) | §§ | §§ | §§
7 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
7 | Anemias(D50–D64) | §§ | §§ | §§
7 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
7 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
7 | Peptic ulcer(K25–K28) | §§ | §§ | §§
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
7 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 36 | 10.0 | 4.9
| Asian, non-Hispanic, male, 25–34
… | All causes | 972 | 100.0 | 56.8
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 317 | 32.6 | 18.5
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 236 | 24.3 | 13.8
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 79 | 8.1 | 4.6
4 | Malignant neoplasms(C00–C97) | 67 | 6.9 | 3.9
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 36 | 3.7 | 2.1
6 | Cerebrovascular diseases(I60–I69) | 26 | 2.7 | 1.5
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 17 | 1.7 | 1.0
8 | Diabetes mellitus(E10–E14) | 15 | 1.5 | 0.9
9 | Influenza and pneumonia(J09–J18) | 10 | 1.0 | 0.6
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 162 | 16.7 | 9.5
| Asian, non-Hispanic, male, 35–44
… | All causes | 1,621 | 100.0 | 91.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 388 | 23.9 | 21.9
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 260 | 16.0 | 14.7
3 | Malignant neoplasms(C00–C97) | 227 | 14.0 | 12.8
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 182 | 11.2 | 10.3
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 81 | 5.0 | 4.6
6 | Cerebrovascular diseases(I60–I69) | 68 | 4.2 | 3.8
7 | Diabetes mellitus(E10–E14) | 59 | 3.6 | 3.3
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 36 | 2.2 | 2.0
9 | Aortic aneurysm and dissection(I71) | 14 | 0.9 | 0.8
9 | Influenza and pneumonia(J09–J18) | 14 | 0.9 | 0.8
… | All other causes(residual) | 292 | 18.0 | 16.5
| Asian, non-Hispanic, male, 45–54
… | All causes | 2,812 | 100.0 | 196.8
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 672 | 23.9 | 47.0
2 | Malignant neoplasms(C00–C97) | 605 | 21.5 | 42.4
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 354 | 12.6 | 24.8
4 | Cerebrovascular diseases(I60–I69) | 190 | 6.8 | 13.3
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 144 | 5.1 | 10.1
6 | Diabetes mellitus(E10–E14) | 141 | 5.0 | 9.9
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 98 | 3.5 | 6.9
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 50 | 1.8 | 3.5
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 43 | 1.5 | 3.0
10 | Influenza and pneumonia(J09–J18) | 31 | 1.1 | 2.2
… | All other causes(residual) | 484 | 17.2 | 33.9
| Asian, non-Hispanic, male, 55–64
… | All causes | 5,149 | 100.0 | 457.7
1 | Malignant neoplasms(C00–C97) | 1,621 | 31.5 | 144.1
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,217 | 23.6 | 108.2
3 | Cerebrovascular diseases(I60–I69) | 295 | 5.7 | 26.2
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 283 | 5.5 | 25.2
5 | Diabetes mellitus(E10–E14) | 277 | 5.4 | 24.6
6 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 147 | 2.9 | 13.1
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 144 | 2.8 | 12.8
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 99 | 1.9 | 8.8
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 76 | 1.5 | 6.8
10 | Influenza and pneumonia(J09–J18) | 72 | 1.4 | 6.4
… | All other causes(residual) | 918 | 17.8 | 81.6
| Asian, non-Hispanic, male, 65 and older
… | All causes | 33,449 | 100.0 | 2,407.8
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 7,661 | 22.9 | 551.5
2 | Malignant neoplasms(C00–C97) | 7,619 | 22.8 | 548.5
3 | Cerebrovascular diseases(I60–I69) | 2,434 | 7.3 | 175.2
4 | Diabetes mellitus(E10–E14) | 1,597 | 4.8 | 115.0
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,139 | 3.4 | 82.0
6 | Alzheimer disease(G30) | 1,059 | 3.2 | 76.2
7 | Chronic lower respiratory diseases(J40–J47) | 1,024 | 3.1 | 73.7
8 | Influenza and pneumonia(J09–J18) | 993 | 3.0 | 71.5
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 880 | 2.6 | 63.3
10 | Parkinson disease(G20–G21) | 748 | 2.2 | 53.8
… | All other causes(residual) | 8,295 | 24.8 | 597.1
| Asian, non-Hispanic, male, 65–74
… | All causes | 8,879 | 100.0 | 1,075.5
1 | Malignant neoplasms(C00–C97) | 2,828 | 31.9 | 342.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,991 | 22.4 | 241.2
3 | Cerebrovascular diseases(I60–I69) | 536 | 6.0 | 64.9
4 | Diabetes mellitus(E10–E14) | 489 | 5.5 | 59.2
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 309 | 3.5 | 37.4
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 219 | 2.5 | 26.5
7 | Influenza and pneumonia(J09–J18) | 198 | 2.2 | 24.0
8 | Chronic lower respiratory diseases(J40–J47) | 194 | 2.2 | 23.5
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 145 | 1.6 | 17.6
10 | Parkinson disease(G20–G21) | 125 | 1.4 | 15.1
… | All other causes(residual) | 1,845 | 20.8 | 223.5
| Asian, non-Hispanic, male, 75–84
… | All causes | 11,838 | 100.0 | 2,822.2
1 | Malignant neoplasms(C00–C97) | 2,931 | 24.8 | 698.8
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 2,626 | 22.2 | 626.0
3 | Cerebrovascular diseases(I60–I69) | 793 | 6.7 | 189.1
4 | Diabetes mellitus(E10–E14) | 623 | 5.3 | 148.5
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 407 | 3.4 | 97.0
6 | Chronic lower respiratory diseases(J40–J47) | 375 | 3.2 | 89.4
7 | Influenza and pneumonia(J09–J18) | 321 | 2.7 | 76.5
8 | Parkinson disease(G20–G21) | 317 | 2.7 | 75.6
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 299 | 2.5 | 71.3
10 | Alzheimer disease(G30) | 290 | 2.4 | 69.1
… | All other causes(residual) | 2,856 | 24.1 | 680.9
| Asian, non-Hispanic, male, 85 and older
… | All causes | 12,732 | 100.0 | 8,830.9
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 3,044 | 23.9 | 2,111.3
2 | Malignant neoplasms(C00–C97) | 1,860 | 14.6 | 1,290.1
3 | Cerebrovascular diseases(I60–I69) | 1,105 | 8.7 | 766.4
4 | Alzheimer disease(G30) | 689 | 5.4 | 477.9
5 | Diabetes mellitus(E10–E14) | 485 | 3.8 | 336.4
6 | Influenza and pneumonia(J09–J18) | 474 | 3.7 | 328.8
7 | Chronic lower respiratory diseases(J40–J47) | 455 | 3.6 | 315.6
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 423 | 3.3 | 293.4
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 362 | 2.8 | 251.1
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 324 | 2.5 | 224.7
… | All other causes(residual) | 3,511 | 27.6 | 2,435.2
| Asian, non-Hispanic, female, all ages^††^
… | All causes | 42,610 | 100.0 | 371.4
1 | Malignant neoplasms(C00–C97) | 10,358 | 24.3 | 90.3
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 7,827 | 18.4 | 68.2
3 | Cerebrovascular diseases(I60–I69) | 3,642 | 8.5 | 31.7
4 | Alzheimer disease(G30) | 2,359 | 5.5 | 20.6
5 | Diabetes mellitus(E10–E14) | 1,775 | 4.2 | 15.5
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,487 | 3.5 | 13.0
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 979 | 2.3 | 8.5
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 917 | 2.2 | 8.0
9 | Influenza and pneumonia(J09–J18) | 890 | 2.1 | 7.8
10 | Chronic lower respiratory diseases(J40–J47) | 733 | 1.7 | 6.4
… | All other causes(residual) | 11,643 | 27.3 | 101.5
| Asian, non-Hispanic, female, 1–4
… | All causes | 61 | 100.0 | 14.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 17 | 27.9 | 3.9
2 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
5 | Septicemia(A40–A41) | §§ | §§ | §§
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
7 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | Certain conditions originating in the perinatal period(P00–P96) | §§ | §§ | §§
8 | COVID-19(*U07.1) | §§ | §§ | §§
8 | Complications of medical and surgical care(Y40–Y84,Y88) | §§ | §§ | §§
… | All other causes(residual) | 14 | 23.0 | 3.2
| Asian, non-Hispanic, female, 5–9
… | All causes | 45 | 100.0 | 7.5
1 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
6 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
6 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
… | All other causes(residual) | 18 | 40.0 | 3.0
| Asian, non-Hispanic, female, 10–14
… | All causes | 46 | 100.0 | 7.8
1 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
1 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
4 | Complications of medical and surgical care(Y40–Y84,Y88) | §§ | §§ | §§
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
6 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
6 | Hernia(K40–K46) | §§ | §§ | §§
6 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
… | All other causes(residual) | 13 | 28.3 | 2.2
| Asian, non-Hispanic, female, 15–19
… | All causes | 115 | 100.0 | 18.8
1 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 42 | 36.5 | 6.9
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 24 | 20.9 | 3.9
3 | Malignant neoplasms(C00–C97) | 14 | 12.2 | 2.3
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
6 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
7 | Complications of medical and surgical care(Y40–Y84,Y88) | §§ | §§ | §§
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
8 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
… | All other causes(residual) | 14 | 12.2 | 2.3
| Asian, non-Hispanic, female, 20–24
… | All causes | 149 | 100.0 | 20.8
1 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 56 | 37.6 | 7.8
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 34 | 22.8 | 4.7
3 | Malignant neoplasms(C00–C97) | 15 | 10.1 | 2.1
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
5 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
7 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
9 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
9 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
9 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
9 | Cholelithiasis and other disorders of gallbladder(K80–K82) | §§ | §§ | §§
… | All other causes(residual) | 22 | 14.8 | 3.1
| Asian, non-Hispanic, female, 25–34
… | All causes | 454 | 100.0 | 25.2
1 | Malignant neoplasms(C00–C97) | 100 | 22.0 | 5.6
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 81 | 17.8 | 4.5
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 70 | 15.4 | 3.9
4 | Pregnancy, childbirth and the puerperium(O00–O99) | 33 | 7.3 | 1.8
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 23 | 5.1 | 1.3
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 20 | 4.4 | 1.1
7 | Cerebrovascular diseases(I60–I69) | 13 | 2.9 | 0.7
8 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 12 | 2.6 | 0.7
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
10 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
… | All other causes(residual) | 88 | 19.4 | 4.9
| Asian, non-Hispanic, female, 35–44
… | All causes | 851 | 100.0 | 44.6
1 | Malignant neoplasms(C00–C97) | 340 | 40.0 | 17.8
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 87 | 10.2 | 4.6
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 62 | 7.3 | 3.3
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 58 | 6.8 | 3.0
5 | Cerebrovascular diseases(I60–I69) | 36 | 4.2 | 1.9
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 34 | 4.0 | 1.8
7 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 21 | 2.5 | 1.1
8 | Diabetes mellitus(E10–E14) | 19 | 2.2 | 1.0
9 | Pregnancy, childbirth and the puerperium(O00–O99) | 17 | 2.0 | 0.9
10 | Influenza and pneumonia(J09–J18) | 12 | 1.4 | 0.6
… | All other causes(residual) | 165 | 19.4 | 8.7
| Asian, non-Hispanic, female, 45–54
… | All causes | 1,815 | 100.0 | 112.8
1 | Malignant neoplasms(C00–C97) | 913 | 50.3 | 56.7
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 148 | 8.2 | 9.2
3 | Cerebrovascular diseases(I60–I69) | 122 | 6.7 | 7.6
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 97 | 5.3 | 6.0
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 79 | 4.4 | 4.9
6 | Diabetes mellitus(E10–E14) | 55 | 3.0 | 3.4
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 38 | 2.1 | 2.4
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 24 | 1.3 | 1.5
9 | Influenza and pneumonia(J09–J18) | 17 | 0.9 | 1.1
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 16 | 0.9 | 1.0
… | All other causes(residual) | 306 | 16.9 | 19.0
| Asian, non-Hispanic, female, 55–64
… | All causes | 3,316 | 100.0 | 254.8
1 | Malignant neoplasms(C00–C97) | 1,692 | 51.0 | 130.0
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 409 | 12.3 | 31.4
3 | Cerebrovascular diseases(I60–I69) | 210 | 6.3 | 16.1
4 | Diabetes mellitus(E10–E14) | 127 | 3.8 | 9.8
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 111 | 3.3 | 8.5
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 61 | 1.8 | 4.7
7 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 53 | 1.6 | 4.1
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | 52 | 1.6 | 4.0
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 42 | 1.3 | 3.2
10 | Influenza and pneumonia(J09–J18) | 41 | 1.2 | 3.2
… | All other causes(residual) | 518 | 15.6 | 39.8
| Asian, non-Hispanic, female, 65 and older
… | All causes | 35,431 | 100.0 | 1,964.0
1 | Malignant neoplasms(C00–C97) | 7,256 | 20.5 | 402.2
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 7,156 | 20.2 | 396.7
3 | Cerebrovascular diseases(I60–I69) | 3,251 | 9.2 | 180.2
4 | Alzheimer disease(G30) | 2,346 | 6.6 | 130.0
5 | Diabetes mellitus(E10–E14) | 1,566 | 4.4 | 86.8
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,027 | 2.9 | 56.9
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 913 | 2.6 | 50.6
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 813 | 2.3 | 45.1
9 | Influenza and pneumonia(J09–J18) | 812 | 2.3 | 45.0
10 | Chronic lower respiratory diseases(J40–J47) | 687 | 1.9 | 38.1
… | All other causes(residual) | 9,604 | 27.1 | 532.4
| Asian, non-Hispanic, female, 65–74
… | All causes | 6,432 | 100.0 | 621.6
1 | Malignant neoplasms(C00–C97) | 2,523 | 39.2 | 243.8
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,000 | 15.5 | 96.6
3 | Cerebrovascular diseases(I60–I69) | 459 | 7.1 | 44.4
4 | Diabetes mellitus(E10–E14) | 350 | 5.4 | 33.8
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 187 | 2.9 | 18.1
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 149 | 2.3 | 14.4
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 108 | 1.7 | 10.4
8 | Influenza and pneumonia(J09–J18) | 95 | 1.5 | 9.2
9 | Chronic lower respiratory diseases(J40–J47) | 94 | 1.5 | 9.1
10 | Alzheimer disease(G30) | 83 | 1.3 | 8.0
… | All other causes(residual) | 1,384 | 21.5 | 133.8
| Asian, non-Hispanic, female, 75–84
… | All causes | 10,884 | 100.0 | 1,988.2
1 | Malignant neoplasms(C00–C97) | 2,714 | 24.9 | 495.8
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,990 | 18.3 | 363.5
3 | Cerebrovascular diseases(I60–I69) | 963 | 8.8 | 175.9
4 | Diabetes mellitus(E10–E14) | 580 | 5.3 | 105.9
5 | Alzheimer disease(G30) | 447 | 4.1 | 81.7
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 355 | 3.3 | 64.8
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 294 | 2.7 | 53.7
8 | Influenza and pneumonia(J09–J18) | 256 | 2.4 | 46.8
9 | Parkinson disease(G20–G21) | 242 | 2.2 | 44.2
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 237 | 2.2 | 43.3
… | All other causes(residual) | 2,806 | 25.8 | 512.6
| Asian, non-Hispanic, female, 85 and older
… | All causes | 18,115 | 100.0 | 8,167.3
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 4,166 | 23.0 | 1,878.3
2 | Malignant neoplasms(C00–C97) | 2,019 | 11.1 | 910.3
3 | Cerebrovascular diseases(I60–I69) | 1,829 | 10.1 | 824.6
4 | Alzheimer disease(G30) | 1,816 | 10.0 | 818.8
5 | Diabetes mellitus(E10–E14) | 636 | 3.5 | 286.7
6 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 568 | 3.1 | 256.1
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 485 | 2.7 | 218.7
8 | Influenza and pneumonia(J09–J18) | 461 | 2.5 | 207.8
9 | Chronic lower respiratory diseases(J40–J47) | 380 | 2.1 | 171.3
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 370 | 2.0 | 166.8
… | All other causes(residual) | 5,385 | 29.7 | 2,427.9
| Black, non-Hispanic, both sexes, all ages^††^
… | All causes | 380,945 | 100.0 | 886.9
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 86,693 | 22.8 | 201.8
2 | Malignant neoplasms(C00–C97) | 72,666 | 19.1 | 169.2
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 28,556 | 7.5 | 66.5
4 | Cerebrovascular diseases(I60–I69) | 22,946 | 6.0 | 53.4
5 | Diabetes mellitus(E10–E14) | 16,674 | 4.4 | 38.8
6 | Chronic lower respiratory diseases(J40–J47) | 11,374 | 3.0 | 26.5
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 10,601 | 2.8 | 24.7
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 10,294 | 2.7 | 24.0
9 | Alzheimer disease(G30) | 8,881 | 2.3 | 20.7
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 7,542 | 2.0 | 17.6
… | All other causes(residual) | 104,718 | 27.5 | 243.8
| Black, non-Hispanic, both sexes, 1–4
… | All causes | 1,078 | 100.0 | 50.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 335 | 31.1 | 15.8
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 111 | 10.3 | 5.2
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 98 | 9.1 | 4.6
4 | Malignant neoplasms(C00–C97) | 48 | 4.5 | 2.3
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 47 | 4.4 | 2.2
6 | Certain conditions originating in the perinatal period(P00–P96) | 29 | 2.7 | 1.4
7 | Influenza and pneumonia(J09–J18) | 25 | 2.3 | 1.2
8 | Chronic lower respiratory diseases(J40–J47) | 22 | 2.0 | 1.0
8 | Cerebrovascular diseases(I60–I69) | 22 | 2.0 | 1.0
10 | COVID-19(*U07.1) | 14 | 1.3 | 0.7
… | All other causes(residual) | 327 | 30.3 | 15.5
| Black, non-Hispanic, both sexes, 5–9
… | All causes | 644 | 100.0 | 23.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 168 | 26.1 | 6.0
2 | Malignant neoplasms(C00–C97) | 72 | 11.2 | 2.6
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 59 | 9.2 | 2.1
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 47 | 7.3 | 1.7
5 | Chronic lower respiratory diseases(J40–J47) | 32 | 5.0 | 1.1
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 25 | 3.9 | 0.9
7 | Influenza and pneumonia(J09–J18) | 21 | 3.3 | 0.8
8 | Anemias(D50–D64) | 11 | 1.7 | 0.4
8 | Cerebrovascular diseases(I60–I69) | 11 | 1.7 | 0.4
10 | Septicemia(A40–A41) | §§ | §§ | §§
10 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 180 | 28.0 | 6.5
| Black, non-Hispanic, both sexes, 10–14
… | All causes | 784 | 100.0 | 27.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 164 | 20.9 | 5.7
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 142 | 18.1 | 4.9
3 | Malignant neoplasms(C00–C97) | 64 | 8.2 | 2.2
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 60 | 7.7 | 2.1
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 47 | 6.0 | 1.6
6 | Chronic lower respiratory diseases(J40–J47) | 42 | 5.4 | 1.5
7 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 26 | 3.3 | 0.9
8 | Influenza and pneumonia(J09–J18) | 15 | 1.9 | 0.5
9 | Cerebrovascular diseases(I60–I69) | 13 | 1.7 | 0.5
10 | Septicemia(A40–A41) | §§ | §§ | §§
10 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
… | All other causes(residual) | 197 | 25.1 | 6.9
| Black, non-Hispanic, both sexes, 15–19
… | All causes | 2,938 | 100.0 | 96.0
1 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 1,368 | 46.6 | 44.7
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 628 | 21.4 | 20.5
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 265 | 9.0 | 8.7
4 | Malignant neoplasms(C00–C97) | 95 | 3.2 | 3.1
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 92 | 3.1 | 3.0
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 40 | 1.4 | 1.3
7 | Chronic lower respiratory diseases(J40–J47) | 37 | 1.3 | 1.2
8 | Legal intervention(Y35,Y89.0) | 22 | 0.7 | 0.7
9 | Diabetes mellitus(E10–E14) | 19 | 0.6 | 0.6
10 | Influenza and pneumonia(J09–J18) | 18 | 0.6 | 0.6
… | All other causes(residual) | 354 | 12.0 | 11.6
| Black, non-Hispanic, both sexes, 20–24
… | All causes | 4,676 | 100.0 | 154.8
1 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 1,637 | 35.0 | 54.2
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,284 | 27.5 | 42.5
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 629 | 13.5 | 20.8
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 155 | 3.3 | 5.1
5 | Malignant neoplasms(C00–C97) | 110 | 2.4 | 3.6
6 | Diabetes mellitus(E10–E14) | 52 | 1.1 | 1.7
7 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 47 | 1.0 | 1.6
8 | Chronic lower respiratory diseases(J40–J47) | 46 | 1.0 | 1.5
9 | Pregnancy, childbirth and the puerperium(O00–O99) | 38 | 0.8 | 1.3
10 | Anemias(D50–D64) | 35 | 0.7 | 1.2
… | All other causes(residual) | 643 | 13.8 | 21.3
| Black, non-Hispanic, both sexes, 25–34
… | All causes | 13,597 | 100.0 | 205.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,256 | 31.3 | 64.3
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 2,831 | 20.8 | 42.7
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,123 | 8.3 | 17.0
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,046 | 7.7 | 15.8
5 | Malignant neoplasms(C00–C97) | 623 | 4.6 | 9.4
6 | Diabetes mellitus(E10–E14) | 359 | 2.6 | 5.4
7 | Human immunodeficiency virus (HIV) disease(B20–B24) | 199 | 1.5 | 3.0
8 | Pregnancy, childbirth and the puerperium(O00–O99) | 150 | 1.1 | 2.3
9 | Cerebrovascular diseases(I60–I69) | 147 | 1.1 | 2.2
10 | Chronic lower respiratory diseases(J40–J47) | 138 | 1.0 | 2.1
… | All other causes(residual) | 2,725 | 20.0 | 41.1
| Black, non-Hispanic, both sexes, 35–44
… | All causes | 20,372 | 100.0 | 342.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,867 | 23.9 | 81.9
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 3,523 | 17.3 | 59.3
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 2,029 | 10.0 | 34.1
4 | Malignant neoplasms(C00–C97) | 2,004 | 9.8 | 33.7
5 | Diabetes mellitus(E10–E14) | 757 | 3.7 | 12.7
6 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 712 | 3.5 | 12.0
7 | Cerebrovascular diseases(I60–I69) | 585 | 2.9 | 9.8
8 | Human immunodeficiency virus (HIV) disease(B20–B24) | 389 | 1.9 | 6.5
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | 385 | 1.9 | 6.5
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 304 | 1.5 | 5.1
… | All other causes(residual) | 4,817 | 23.6 | 81.0
| Black, non-Hispanic, both sexes, 45–54
… | All causes | 30,763 | 100.0 | 602.1
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 7,352 | 23.9 | 143.9
2 | Malignant neoplasms(C00–C97) | 5,183 | 16.8 | 101.4
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,385 | 14.3 | 85.8
4 | Diabetes mellitus(E10–E14) | 1,544 | 5.0 | 30.2
5 | Cerebrovascular diseases(I60–I69) | 1,328 | 4.3 | 26.0
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 1,119 | 3.6 | 21.9
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 754 | 2.5 | 14.8
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | 648 | 2.1 | 12.7
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 631 | 2.1 | 12.3
10 | Septicemia(A40–A41) | 517 | 1.7 | 10.1
… | All other causes(residual) | 7,302 | 23.7 | 142.9
| Black, non-Hispanic, both sexes, 55–64
… | All causes | 62,102 | 100.0 | 1,248.0
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 15,334 | 24.7 | 308.2
2 | Malignant neoplasms(C00–C97) | 14,717 | 23.7 | 295.8
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 5,608 | 9.0 | 112.7
4 | Diabetes mellitus(E10–E14) | 3,261 | 5.3 | 65.5
5 | Cerebrovascular diseases(I60–I69) | 3,231 | 5.2 | 64.9
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,670 | 2.7 | 33.6
7 | Chronic lower respiratory diseases(J40–J47) | 1,633 | 2.6 | 32.8
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,205 | 1.9 | 24.2
9 | Septicemia(A40–A41) | 1,178 | 1.9 | 23.7
10 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,117 | 1.8 | 22.4
… | All other causes(residual) | 13,148 | 21.2 | 264.2
| Black, non-Hispanic, both sexes, 65 and older
… | All causes | 238,619 | 100.0 | 4,020.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 58,939 | 24.7 | 993.1
2 | Malignant neoplasms(C00–C97) | 49,743 | 20.8 | 838.1
3 | Cerebrovascular diseases(I60–I69) | 17,549 | 7.4 | 295.7
4 | Diabetes mellitus(E10–E14) | 10,667 | 4.5 | 179.7
5 | Chronic lower respiratory diseases(J40–J47) | 8,801 | 3.7 | 148.3
6 | Alzheimer disease(G30) | 8,751 | 3.7 | 147.4
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 7,722 | 3.2 | 130.1
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 6,429 | 2.7 | 108.3
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 5,369 | 2.3 | 90.5
10 | Septicemia(A40–A41) | 4,726 | 2.0 | 79.6
… | All other causes(residual) | 59,923 | 25.1 | 1,009.7
| Black, non-Hispanic, both sexes, 65–74
… | All causes | 93,317 | 100.0 | 2,494.6
1 | Malignant neoplasms(C00–C97) | 24,142 | 25.9 | 645.4
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 22,998 | 24.6 | 614.8
3 | Cerebrovascular diseases(I60–I69) | 5,656 | 6.1 | 151.2
4 | Diabetes mellitus(E10–E14) | 4,639 | 5.0 | 124.0
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3,787 | 4.1 | 101.2
6 | Chronic lower respiratory diseases(J40–J47) | 3,687 | 4.0 | 98.6
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 2,806 | 3.0 | 75.0
8 | Septicemia(A40–A41) | 1,983 | 2.1 | 53.0
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,968 | 2.1 | 52.6
10 | Influenza and pneumonia(J09–J18) | 1,460 | 1.6 | 39.0
… | All other causes(residual) | 20,191 | 21.6 | 539.8
| Black, non-Hispanic, both sexes, 75–84
… | All causes | 80,400 | 100.0 | 4,819.0
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 19,342 | 24.1 | 1,159.3
2 | Malignant neoplasms(C00–C97) | 17,197 | 21.4 | 1,030.7
3 | Cerebrovascular diseases(I60–I69) | 6,064 | 7.5 | 363.5
4 | Diabetes mellitus(E10–E14) | 3,744 | 4.7 | 224.4
5 | Chronic lower respiratory diseases(J40–J47) | 3,210 | 4.0 | 192.4
6 | Alzheimer disease(G30) | 2,954 | 3.7 | 177.1
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 2,900 | 3.6 | 173.8
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,755 | 2.2 | 105.2
9 | Septicemia(A40–A41) | 1,710 | 2.1 | 102.5
10 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,609 | 2.0 | 96.4
… | All other causes(residual) | 19,915 | 24.8 | 1,193.7
| Black, non-Hispanic, both sexes, 85 and older
… | All causes | 64,902 | 100.0 | 12,342.1
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 16,599 | 25.6 | 3,156.5
2 | Malignant neoplasms(C00–C97) | 8,404 | 12.9 | 1,598.1
3 | Cerebrovascular diseases(I60–I69) | 5,829 | 9.0 | 1,108.5
4 | Alzheimer disease(G30) | 4,801 | 7.4 | 913.0
5 | Diabetes mellitus(E10–E14) | 2,284 | 3.5 | 434.3
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 2,016 | 3.1 | 383.4
7 | Chronic lower respiratory diseases(J40–J47) | 1,904 | 2.9 | 362.1
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,646 | 2.5 | 313.0
9 | Influenza and pneumonia(J09–J18) | 1,102 | 1.7 | 209.6
10 | Nutritional deficiencies(E40–E64) | 1,061 | 1.6 | 201.8
… | All other causes(residual) | 19,256 | 29.7 | 3,661.8
| Black, non-Hispanic, male, all ages^††^
… | All causes | 201,255 | 100.0 | 976.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 47,085 | 23.4 | 228.5
2 | Malignant neoplasms(C00–C97) | 36,172 | 18.0 | 175.6
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 20,250 | 10.1 | 98.3
4 | Cerebrovascular diseases(I60–I69) | 10,424 | 5.2 | 50.6
5 | Diabetes mellitus(E10–E14) | 8,850 | 4.4 | 43.0
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 8,784 | 4.4 | 42.6
7 | Chronic lower respiratory diseases(J40–J47) | 5,723 | 2.8 | 27.8
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 5,205 | 2.6 | 25.3
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 3,630 | 1.8 | 17.6
10 | Septicemia(A40–A41) | 3,259 | 1.6 | 15.8
… | All other causes(residual) | 51,873 | 25.8 | 251.8
| Black, non-Hispanic, male, 1–4
… | All causes | 622 | 100.0 | 58.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 209 | 33.6 | 19.5
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 64 | 10.3 | 6.0
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 55 | 8.8 | 5.1
4 | Malignant neoplasms(C00–C97) | 28 | 4.5 | 2.6
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 23 | 3.7 | 2.1
6 | Certain conditions originating in the perinatal period(P00–P96) | 16 | 2.6 | 1.5
7 | Chronic lower respiratory diseases(J40–J47) | 14 | 2.3 | 1.3
8 | Cerebrovascular diseases(I60–I69) | 13 | 2.1 | 1.2
9 | Influenza and pneumonia(J09–J18) | 12 | 1.9 | 1.1
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 179 | 28.8 | 16.7
| Black, non-Hispanic, male, 5–9
… | All causes | 389 | 100.0 | 27.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 105 | 27.0 | 7.5
2 | Malignant neoplasms(C00–C97) | 46 | 11.8 | 3.3
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 40 | 10.3 | 2.8
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 24 | 6.2 | 1.7
5 | Chronic lower respiratory diseases(J40–J47) | 17 | 4.4 | 1.2
6 | Influenza and pneumonia(J09–J18) | 14 | 3.6 | 1.0
7 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 13 | 3.3 | 0.9
8 | Anemias(D50–D64) | §§ | §§ | §§
8 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
10 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
… | All other causes(residual) | 108 | 27.8 | 7.7
| Black, non-Hispanic, male, 10–14
… | All causes | 486 | 100.0 | 33.3
1 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 109 | 22.4 | 7.5
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 105 | 21.6 | 7.2
3 | Malignant neoplasms(C00–C97) | 36 | 7.4 | 2.5
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 30 | 6.2 | 2.1
5 | Chronic lower respiratory diseases(J40–J47) | 25 | 5.1 | 1.7
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 21 | 4.3 | 1.4
7 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 14 | 2.9 | 1.0
8 | Cerebrovascular diseases(I60–I69) | 10 | 2.1 | 0.7
9 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 123 | 25.3 | 8.4
| Black, non-Hispanic, male, 15–19
… | All causes | 2,271 | 100.0 | 146.3
1 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 1,209 | 53.2 | 77.9
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 466 | 20.5 | 30.0
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 195 | 8.6 | 12.6
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 63 | 2.8 | 4.1
5 | Malignant neoplasms(C00–C97) | 56 | 2.5 | 3.6
6 | Chronic lower respiratory diseases(J40–J47) | 25 | 1.1 | 1.6
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 25 | 1.1 | 1.6
8 | Legal intervention(Y35,Y89.0) | 20 | 0.9 | 1.3
9 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 195 | 8.6 | 12.6
| Black, non-Hispanic, male, 20–24
… | All causes | 3,517 | 100.0 | 231.6
1 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 1,427 | 40.6 | 94.0
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 909 | 25.8 | 59.9
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 513 | 14.6 | 33.8
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 107 | 3.0 | 7.0
5 | Malignant neoplasms(C00–C97) | 58 | 1.6 | 3.8
6 | Chronic lower respiratory diseases(J40–J47) | 31 | 0.9 | 2.0
7 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 29 | 0.8 | 1.9
8 | Diabetes mellitus(E10–E14) | 27 | 0.8 | 1.8
9 | Anemias(D50–D64) | 19 | 0.5 | 1.3
10 | Legal intervention(Y35,Y89.0) | 16 | 0.5 | 1.1
… | All other causes(residual) | 381 | 10.8 | 25.1
| Black, non-Hispanic, male, 25–34
… | All causes | 9,476 | 100.0 | 287.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3,031 | 32.0 | 91.8
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 2,447 | 25.8 | 74.1
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 845 | 8.9 | 25.6
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 730 | 7.7 | 22.1
5 | Malignant neoplasms(C00–C97) | 273 | 2.9 | 8.3
6 | Diabetes mellitus(E10–E14) | 209 | 2.2 | 6.3
7 | Human immunodeficiency virus (HIV) disease(B20–B24) | 157 | 1.7 | 4.8
8 | Influenza and pneumonia(J09–J18) | 87 | 0.9 | 2.6
9 | Chronic lower respiratory diseases(J40–J47) | 80 | 0.8 | 2.4
10 | Cerebrovascular diseases(I60–I69) | 77 | 0.8 | 2.3
… | All other causes(residual) | 1,540 | 16.3 | 46.7
| Black, non-Hispanic, male, 35–44
… | All causes | 13,064 | 100.0 | 454.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3,562 | 27.3 | 123.8
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 2,283 | 17.5 | 79.3
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 1,766 | 13.5 | 61.4
4 | Malignant neoplasms(C00–C97) | 819 | 6.3 | 28.5
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 584 | 4.5 | 20.3
6 | Diabetes mellitus(E10–E14) | 438 | 3.4 | 15.2
7 | Cerebrovascular diseases(I60–I69) | 305 | 2.3 | 10.6
8 | Human immunodeficiency virus (HIV) disease(B20–B24) | 281 | 2.2 | 9.8
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | 195 | 1.5 | 6.8
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 177 | 1.4 | 6.2
… | All other causes(residual) | 2,654 | 20.3 | 92.2
| Black, non-Hispanic, male, 45–54
… | All causes | 18,717 | 100.0 | 777.8
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 4,815 | 25.7 | 200.1
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3,215 | 17.2 | 133.6
3 | Malignant neoplasms(C00–C97) | 2,422 | 12.9 | 100.6
4 | Diabetes mellitus(E10–E14) | 952 | 5.1 | 39.6
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 947 | 5.1 | 39.4
6 | Cerebrovascular diseases(I60–I69) | 712 | 3.8 | 29.6
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 454 | 2.4 | 18.9
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 404 | 2.2 | 16.8
9 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 371 | 2.0 | 15.4
10 | Chronic liver disease and cirrhosis(K70,K73–K74) | 357 | 1.9 | 14.8
… | All other causes(residual) | 4,068 | 21.7 | 169.0
| Black, non-Hispanic, male, 55–64
… | All causes | 36,602 | 100.0 | 1,590.1
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 9,846 | 26.9 | 427.7
2 | Malignant neoplasms(C00–C97) | 7,310 | 20.0 | 317.6
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,193 | 11.5 | 182.2
4 | Diabetes mellitus(E10–E14) | 1,959 | 5.4 | 85.1
5 | Cerebrovascular diseases(I60–I69) | 1,893 | 5.2 | 82.2
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 977 | 2.7 | 42.4
7 | Chronic lower respiratory diseases(J40–J47) | 782 | 2.1 | 34.0
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | 717 | 2.0 | 31.1
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 699 | 1.9 | 30.4
10 | Septicemia(A40–A41) | 630 | 1.7 | 27.4
… | All other causes(residual) | 7,596 | 20.8 | 330.0
| Black, non-Hispanic, male, 65 and older
… | All causes | 113,161 | 100.0 | 4,619.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 29,149 | 25.8 | 1,189.9
2 | Malignant neoplasms(C00–C97) | 25,119 | 22.2 | 1,025.4
3 | Cerebrovascular diseases(I60–I69) | 7,377 | 6.5 | 301.1
4 | Diabetes mellitus(E10–E14) | 5,247 | 4.6 | 214.2
5 | Chronic lower respiratory diseases(J40–J47) | 4,433 | 3.9 | 181.0
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,221 | 3.7 | 172.3
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 3,525 | 3.1 | 143.9
8 | Alzheimer disease(G30) | 2,578 | 2.3 | 105.2
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 2,324 | 2.1 | 94.9
10 | Septicemia(A40–A41) | 2,175 | 1.9 | 88.8
… | All other causes(residual) | 27,013 | 23.9 | 1,102.7
| Black, non-Hispanic, male, 65–74
… | All causes | 52,041 | 100.0 | 3,198.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 13,633 | 26.2 | 837.9
2 | Malignant neoplasms(C00–C97) | 12,738 | 24.5 | 782.9
3 | Cerebrovascular diseases(I60–I69) | 3,063 | 5.9 | 188.3
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 2,783 | 5.3 | 171.1
5 | Diabetes mellitus(E10–E14) | 2,573 | 4.9 | 158.1
6 | Chronic lower respiratory diseases(J40–J47) | 2,005 | 3.9 | 123.2
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,440 | 2.8 | 88.5
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,070 | 2.1 | 65.8
9 | Septicemia(A40–A41) | 1,023 | 2.0 | 62.9
10 | Influenza and pneumonia(J09–J18) | 800 | 1.5 | 49.2
… | All other causes(residual) | 10,913 | 21.0 | 670.8
| Black, non-Hispanic, male, 75–84
… | All causes | 38,579 | 100.0 | 5,890.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 9,742 | 25.3 | 1,487.5
2 | Malignant neoplasms(C00–C97) | 8,686 | 22.5 | 1,326.3
3 | Cerebrovascular diseases(I60–I69) | 2,603 | 6.7 | 397.5
4 | Diabetes mellitus(E10–E14) | 1,806 | 4.7 | 275.8
5 | Chronic lower respiratory diseases(J40–J47) | 1,618 | 4.2 | 247.1
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,320 | 3.4 | 201.6
7 | Alzheimer disease(G30) | 1,004 | 2.6 | 153.3
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 990 | 2.6 | 151.2
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 771 | 2.0 | 117.7
10 | Septicemia(A40–A41) | 764 | 2.0 | 116.7
… | All other causes(residual) | 9,275 | 24.0 | 1,416.2
| Black, non-Hispanic, male, 85 and older
… | All causes | 22,541 | 100.0 | 13,436.9
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 5,774 | 25.6 | 3,441.9
2 | Malignant neoplasms(C00–C97) | 3,695 | 16.4 | 2,202.6
3 | Cerebrovascular diseases(I60–I69) | 1,711 | 7.6 | 1,019.9
4 | Alzheimer disease(G30) | 1,144 | 5.1 | 681.9
5 | Diabetes mellitus(E10–E14) | 868 | 3.9 | 517.4
6 | Chronic lower respiratory diseases(J40–J47) | 810 | 3.6 | 482.8
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 765 | 3.4 | 456.0
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 483 | 2.1 | 287.9
9 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 448 | 2.0 | 267.1
10 | Influenza and pneumonia(J09–J18) | 421 | 1.9 | 251.0
… | All other causes(residual) | 6,422 | 28.5 | 3,828.2
| Black, non-Hispanic, female, all ages^††^
… | All causes | 179,690 | 100.0 | 804.1
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 39,608 | 22.0 | 177.2
2 | Malignant neoplasms(C00–C97) | 36,494 | 20.3 | 163.3
3 | Cerebrovascular diseases(I60–I69) | 12,522 | 7.0 | 56.0
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 8,306 | 4.6 | 37.2
5 | Diabetes mellitus(E10–E14) | 7,824 | 4.4 | 35.0
6 | Alzheimer disease(G30) | 6,244 | 3.5 | 27.9
7 | Chronic lower respiratory diseases(J40–J47) | 5,651 | 3.1 | 25.3
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 5,396 | 3.0 | 24.1
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 3,912 | 2.2 | 17.5
10 | Septicemia(A40–A41) | 3,540 | 2.0 | 15.8
… | All other causes(residual) | 50,193 | 27.9 | 224.6
| Black, non-Hispanic, female, 1–4
… | All causes | 456 | 100.0 | 43.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 126 | 27.6 | 12.1
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 47 | 10.3 | 4.5
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 43 | 9.4 | 4.1
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 24 | 5.3 | 2.3
5 | Malignant neoplasms(C00–C97) | 20 | 4.4 | 1.9
6 | Certain conditions originating in the perinatal period(P00–P96) | 13 | 2.9 | 1.2
6 | Influenza and pneumonia(J09–J18) | 13 | 2.9 | 1.2
8 | Cerebrovascular diseases(I60–I69) | ** | ** | **
9 | Chronic lower respiratory diseases(J40–J47) | ** | ** | **
9 | COVID-19(*U07.1) | ** | ** | **
… | All other causes(residual) | 145 | 31.8 | 13.9
| Black, non-Hispanic, female, 5–9
… | All causes | 255 | 100.0 | 18.5
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 63 | 24.7 | 4.6
2 | Malignant neoplasms(C00–C97) | 26 | 10.2 | 1.9
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 23 | 9.0 | 1.7
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 19 | 7.5 | 1.4
5 | Chronic lower respiratory diseases(J40–J47) | 15 | 5.9 | 1.1
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 12 | 4.7 | 0.9
7 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
8 | Anemias(D50–D64) | §§ | §§ | §§
8 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 75 | 29.4 | 5.4
| Black, non-Hispanic, female, 10–14
… | All causes | 298 | 100.0 | 21.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 59 | 19.8 | 4.2
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 33 | 11.1 | 2.3
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 30 | 10.1 | 2.1
4 | Malignant neoplasms(C00–C97) | 28 | 9.4 | 2.0
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 26 | 8.7 | 1.8
6 | Chronic lower respiratory diseases(J40–J47) | 17 | 5.7 | 1.2
7 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 12 | 4.0 | 0.8
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
9 | Complications of medical and surgical care(Y40–Y84,Y88) | §§ | §§ | §§
10 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
10 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
… | All other causes(residual) | 74 | 24.8 | 5.2
| Black, non-Hispanic, female, 15–19
… | All causes | 667 | 100.0 | 44.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 162 | 24.3 | 10.7
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 159 | 23.8 | 10.5
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 70 | 10.5 | 4.6
4 | Malignant neoplasms(C00–C97) | 39 | 5.8 | 2.6
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 29 | 4.3 | 1.9
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 15 | 2.2 | 1.0
7 | Influenza and pneumonia(J09–J18) | 13 | 1.9 | 0.9
8 | Chronic lower respiratory diseases(J40–J47) | 12 | 1.8 | 0.8
9 | Diabetes mellitus(E10–E14) | 10 | 1.5 | 0.7
10 | Septicemia(A40–A41) | §§ | §§ | §§
10 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
… | All other causes(residual) | 146 | 21.9 | 9.7
| Black, non-Hispanic, female, 20–24
… | All causes | 1,159 | 100.0 | 77.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 375 | 32.4 | 25.0
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 210 | 18.1 | 14.0
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 116 | 10.0 | 7.7
4 | Malignant neoplasms(C00–C97) | 52 | 4.5 | 3.5
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 48 | 4.1 | 3.2
6 | Pregnancy, childbirth and the puerperium(O00–O99) | 38 | 3.3 | 2.5
7 | Diabetes mellitus(E10–E14) | 25 | 2.2 | 1.7
8 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 18 | 1.6 | 1.2
9 | Anemias(D50–D64) | 16 | 1.4 | 1.1
10 | Chronic lower respiratory diseases(J40–J47) | 15 | 1.3 | 1.0
… | All other causes(residual) | 246 | 21.2 | 16.4
| Black, non-Hispanic, female, 25–34
… | All causes | 4,121 | 100.0 | 124.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,225 | 29.7 | 36.9
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 393 | 9.5 | 11.8
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 384 | 9.3 | 11.6
4 | Malignant neoplasms(C00–C97) | 350 | 8.5 | 10.5
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 201 | 4.9 | 6.0
6 | Diabetes mellitus(E10–E14) | 150 | 3.6 | 4.5
6 | Pregnancy, childbirth and the puerperium(O00–O99) | 150 | 3.6 | 4.5
8 | Cerebrovascular diseases(I60–I69) | 70 | 1.7 | 2.1
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 64 | 1.6 | 1.9
10 | Chronic lower respiratory diseases(J40–J47) | 58 | 1.4 | 1.7
… | All other causes(residual) | 1,076 | 26.1 | 32.4
| Black, non-Hispanic, female, 35–44
… | All causes | 7,308 | 100.0 | 238.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,305 | 17.9 | 42.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,240 | 17.0 | 40.4
3 | Malignant neoplasms(C00–C97) | 1,185 | 16.2 | 38.6
4 | Diabetes mellitus(E10–E14) | 319 | 4.4 | 10.4
5 | Cerebrovascular diseases(I60–I69) | 280 | 3.8 | 9.1
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 263 | 3.6 | 8.6
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 190 | 2.6 | 6.2
8 | Pregnancy, childbirth and the puerperium(O00–O99) | 130 | 1.8 | 4.2
9 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 128 | 1.8 | 4.2
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 127 | 1.7 | 4.1
… | All other causes(residual) | 2,141 | 29.3 | 69.8
| Black, non-Hispanic, female, 45–54
… | All causes | 12,046 | 100.0 | 445.6
1 | Malignant neoplasms(C00–C97) | 2,761 | 22.9 | 102.1
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 2,537 | 21.1 | 93.8
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,170 | 9.7 | 43.3
4 | Cerebrovascular diseases(I60–I69) | 616 | 5.1 | 22.8
5 | Diabetes mellitus(E10–E14) | 592 | 4.9 | 21.9
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 300 | 2.5 | 11.1
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 291 | 2.4 | 10.8
8 | Septicemia(A40–A41) | 258 | 2.1 | 9.5
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 227 | 1.9 | 8.4
10 | Chronic lower respiratory diseases(J40–J47) | 207 | 1.7 | 7.7
… | All other causes(residual) | 3,087 | 25.6 | 114.2
| Black, non-Hispanic, female, 55–64
… | All causes | 25,500 | 100.0 | 953.6
1 | Malignant neoplasms(C00–C97) | 7,407 | 29.0 | 277.0
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 5,488 | 21.5 | 205.2
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,415 | 5.5 | 52.9
4 | Cerebrovascular diseases(I60–I69) | 1,338 | 5.2 | 50.0
5 | Diabetes mellitus(E10–E14) | 1,302 | 5.1 | 48.7
6 | Chronic lower respiratory diseases(J40–J47) | 851 | 3.3 | 31.8
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 693 | 2.7 | 25.9
8 | Septicemia(A40–A41) | 548 | 2.1 | 20.5
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 506 | 2.0 | 18.9
10 | Influenza and pneumonia(J09–J18) | 402 | 1.6 | 15.0
… | All other causes(residual) | 5,550 | 21.8 | 207.5
| Black, non-Hispanic, female, 65 and older
… | All causes | 125,458 | 100.0 | 3,599.6
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 29,790 | 23.7 | 854.7
2 | Malignant neoplasms(C00–C97) | 24,624 | 19.6 | 706.5
3 | Cerebrovascular diseases(I60–I69) | 10,172 | 8.1 | 291.8
4 | Alzheimer disease(G30) | 6,173 | 4.9 | 177.1
5 | Diabetes mellitus(E10–E14) | 5,420 | 4.3 | 155.5
6 | Chronic lower respiratory diseases(J40–J47) | 4,368 | 3.5 | 125.3
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 4,197 | 3.3 | 120.4
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 3,045 | 2.4 | 87.4
9 | Septicemia(A40–A41) | 2,551 | 2.0 | 73.2
10 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 2,208 | 1.8 | 63.4
… | All other causes(residual) | 32,910 | 26.2 | 944.2
| Black, non-Hispanic, female, 65–74
… | All causes | 41,276 | 100.0 | 1,952.7
1 | Malignant neoplasms(C00–C97) | 11,404 | 27.6 | 539.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 9,365 | 22.7 | 443.0
3 | Cerebrovascular diseases(I60–I69) | 2,593 | 6.3 | 122.7
4 | Diabetes mellitus(E10–E14) | 2,066 | 5.0 | 97.7
5 | Chronic lower respiratory diseases(J40–J47) | 1,682 | 4.1 | 79.6
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,366 | 3.3 | 64.6
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,004 | 2.4 | 47.5
8 | Septicemia(A40–A41) | 960 | 2.3 | 45.4
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 898 | 2.2 | 42.5
10 | Influenza and pneumonia(J09–J18) | 660 | 1.6 | 31.2
… | All other causes(residual) | 9,278 | 22.5 | 438.9
| Black, non-Hispanic, female, 75–84
… | All causes | 41,821 | 100.0 | 4,126.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 9,600 | 23.0 | 947.2
2 | Malignant neoplasms(C00–C97) | 8,511 | 20.4 | 839.8
3 | Cerebrovascular diseases(I60–I69) | 3,461 | 8.3 | 341.5
4 | Alzheimer disease(G30) | 1,950 | 4.7 | 192.4
5 | Diabetes mellitus(E10–E14) | 1,938 | 4.6 | 191.2
6 | Chronic lower respiratory diseases(J40–J47) | 1,592 | 3.8 | 157.1
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,580 | 3.8 | 155.9
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 984 | 2.4 | 97.1
9 | Septicemia(A40–A41) | 946 | 2.3 | 93.3
10 | Influenza and pneumonia(J09–J18) | 697 | 1.7 | 68.8
… | All other causes(residual) | 10,562 | 25.3 | 1,042.1
| Black, non-Hispanic, female, 85 and older
… | All causes | 42,361 | 100.0 | 11,829.2
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 10,825 | 25.6 | 3,022.9
2 | Malignant neoplasms(C00–C97) | 4,709 | 11.1 | 1,315.0
3 | Cerebrovascular diseases(I60–I69) | 4,118 | 9.7 | 1,149.9
4 | Alzheimer disease(G30) | 3,657 | 8.6 | 1,021.2
5 | Diabetes mellitus(E10–E14) | 1,416 | 3.3 | 395.4
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,251 | 3.0 | 349.3
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 1,163 | 2.7 | 324.8
8 | Chronic lower respiratory diseases(J40–J47) | 1,094 | 2.6 | 305.5
9 | Nutritional deficiencies(E40–E64) | 759 | 1.8 | 211.9
10 | Influenza and pneumonia(J09–J18) | 681 | 1.6 | 190.2
… | All other causes(residual) | 12,688 | 30.0 | 3,543.1
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, all ages^††^
… | All causes | 4,431 | 100.0 | 656.6
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,035 | 23.4 | 153.4
2 | Malignant neoplasms(C00–C97) | 913 | 20.6 | 135.3
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 309 | 7.0 | 45.8
4 | Diabetes mellitus(E10–E14) | 295 | 6.7 | 43.7
5 | Cerebrovascular diseases(I60–I69) | 267 | 6.0 | 39.6
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 142 | 3.2 | 21.0
7 | Chronic lower respiratory diseases(J40–J47) | 98 | 2.2 | 14.5
8 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 96 | 2.2 | 14.2
9 | Alzheimer disease(G30) | 81 | 1.8 | 12.0
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 78 | 1.8 | 11.6
… | All other causes(residual) | 1,117 | 25.2 | 165.5
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 1–4
… | All causes | 16 | 100.0 | 45.7
1 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
1 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
4 | Septicemia(A40–A41) | §§ | §§ | §§
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
4 | Aortic aneurysm and dissection(I71) | §§ | §§ | §§
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 5–9
… | All causes | 12 | 100.0 | 25.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Septicemia(A40–A41) | §§ | §§ | §§
2 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
2 | Acute bronchitis and bronchiolitis(J20–J21) | §§ | §§ | §§
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 10–14
… | All causes | 11 | 100.0 | 24.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
3 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 15–19
… | All causes | 26 | 100.0 | 54.8
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
6 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
6 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
6 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
6 | Legal intervention(Y35,Y89.0) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 20–24
… | All causes | 61 | 100.0 | 127.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 22 | 36.1 | 45.9
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 11 | 18.0 | 22.9
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 10 | 16.4 | 20.8
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
5 | Tuberculosis(A16–A19) | §§ | §§ | §§
5 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
5 | Pneumonitis due to solids and liquids(J69) | §§ | §§ | §§
5 | Pregnancy, childbirth and the puerperium(O00–O99) | §§ | §§ | §§
… | All other causes(residual) | 10 | 16.4 | 20.8
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 25–34
… | All causes | 202 | 100.0 | 199.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 59 | 29.2 | 58.2
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 33 | 16.3 | 32.6
3 | Malignant neoplasms(C00–C97) | 27 | 13.4 | 26.6
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 23 | 11.4 | 22.7
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 13 | 6.4 | 12.8
6 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
7 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
8 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
8 | Septicemia(A40–A41) | §§ | §§ | §§
10 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
10 | Tuberculosis(A16–A19) | §§ | §§ | §§
10 | Viral hepatitis(B15–B19) | §§ | §§ | §§
10 | Human immunodeficiency virus (HIV) disease(B20–B24) | §§ | §§ | §§
10 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
10 | Meningitis(G00,G03) | §§ | §§ | §§
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | §§ | §§ | §§
10 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
10 | Pregnancy, childbirth and the puerperium(O00–O99) | §§ | §§ | §§
10 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 24 | 11.9 | 23.7
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 35–44
… | All causes | 366 | 100.0 | 343.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 76 | 20.8 | 71.2
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 73 | 19.9 | 68.4
3 | Malignant neoplasms(C00–C97) | 61 | 16.7 | 57.2
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 26 | 7.1 | 24.4
5 | Diabetes mellitus(E10–E14) | 16 | 4.4 | 15.0
6 | Cerebrovascular diseases(I60–I69) | 10 | 2.7 | 9.4
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
10 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
… | All other causes(residual) | 75 | 20.5 | 70.3
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 45–54
… | All causes | 559 | 100.0 | 686.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 133 | 23.8 | 163.4
2 | Malignant neoplasms(C00–C97) | 130 | 23.3 | 159.7
3 | Diabetes mellitus(E10–E14) | 43 | 7.7 | 52.8
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 42 | 7.5 | 51.6
5 | Cerebrovascular diseases(I60–I69) | 36 | 6.4 | 44.2
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 19 | 3.4 | 23.3
7 | Influenza and pneumonia(J09–J18) | 14 | 2.5 | 17.2
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 13 | 2.3 | 16.0
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | 10 | 1.8 | 12.3
10 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 101 | 18.1 | 124.1
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 55–64
… | All causes | 845 | 100.0 | 1,186.6
1 | Malignant neoplasms(C00–C97) | 243 | 28.8 | 341.2
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 203 | 24.0 | 285.1
3 | Diabetes mellitus(E10–E14) | 70 | 8.3 | 98.3
4 | Cerebrovascular diseases(I60–I69) | 48 | 5.7 | 67.4
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 47 | 5.6 | 66.0
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 29 | 3.4 | 40.7
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 15 | 1.8 | 21.1
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 15 | 1.8 | 21.1
9 | Influenza and pneumonia(J09–J18) | 13 | 1.5 | 18.3
10 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 12 | 1.4 | 16.9
… | All other causes(residual) | 150 | 17.8 | 210.6
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 65 and older
… | All causes | 2,260 | 100.0 | 2,753.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 596 | 26.4 | 726.2
2 | Malignant neoplasms(C00–C97) | 443 | 19.6 | 539.8
3 | Cerebrovascular diseases(I60–I69) | 171 | 7.6 | 208.4
4 | Diabetes mellitus(E10–E14) | 160 | 7.1 | 195.0
5 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 88 | 3.9 | 107.2
6 | Alzheimer disease(G30) | 79 | 3.5 | 96.3
7 | Chronic lower respiratory diseases(J40–J47) | 75 | 3.3 | 91.4
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 47 | 2.1 | 57.3
9 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 41 | 1.8 | 50.0
10 | Influenza and pneumonia(J09–J18) | 37 | 1.6 | 45.1
… | All other causes(residual) | 523 | 23.1 | 637.2
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 65–74
… | All causes | 990 | 100.0 | 1,966.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 254 | 25.7 | 504.5
2 | Malignant neoplasms(C00–C97) | 236 | 23.8 | 468.8
3 | Diabetes mellitus(E10–E14) | 93 | 9.4 | 184.7
4 | Cerebrovascular diseases(I60–I69) | 74 | 7.5 | 147.0
5 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 39 | 3.9 | 77.5
6 | Chronic lower respiratory diseases(J40–J47) | 34 | 3.4 | 67.5
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 20 | 2.0 | 39.7
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 18 | 1.8 | 35.8
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | 13 | 1.3 | 25.8
10 | COVID-19(*U07.1) | 12 | 1.2 | 23.8
10 | Septicemia(A40–A41) | 12 | 1.2 | 23.8
… | All other causes(residual) | 185 | 18.7 | 367.5
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 75–84
… | All causes | 840 | 100.0 | 3,503.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 238 | 28.3 | 992.7
2 | Malignant neoplasms(C00–C97) | 161 | 19.2 | 671.5
3 | Cerebrovascular diseases(I60–I69) | 53 | 6.3 | 221.1
4 | Diabetes mellitus(E10–E14) | 44 | 5.2 | 183.5
5 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 37 | 4.4 | 154.3
6 | Chronic lower respiratory diseases(J40–J47) | 30 | 3.6 | 125.1
7 | Alzheimer disease(G30) | 25 | 3.0 | 104.3
8 | Influenza and pneumonia(J09–J18) | 20 | 2.4 | 83.4
9 | Septicemia(A40–A41) | 18 | 2.1 | 75.1
10 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 16 | 1.9 | 66.7
… | All other causes(residual) | 198 | 23.6 | 825.8
| Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes, 85 and older
… | All causes | 430 | 100.0 | 5,548.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 104 | 24.2 | 1,341.9
2 | Malignant neoplasms(C00–C97) | 46 | 10.7 | 593.5
3 | Cerebrovascular diseases(I60–I69) | 44 | 10.2 | 567.7
4 | Alzheimer disease(G30) | 43 | 10.0 | 554.8
5 | Diabetes mellitus(E10–E14) | 23 | 5.3 | 296.8
6 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 13 | 3.0 | 167.7
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 12 | 2.8 | 154.8
8 | Chronic lower respiratory diseases(J40–J47) | 11 | 2.6 | 141.9
9 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
10 | Parkinson disease(G20–G21) | §§ | §§ | §§
10 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
10 | COVID-19(*U07.1) | §§ | §§ | §§
10 | Nutritional deficiencies(E40–E64) | §§ | §§ | §§
… | All other causes(residual) | 103 | 24.0 | 1,329.0
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, all ages^††^
… | All causes | 2,431 | 100.0 | 713.9
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 607 | 25.0 | 178.3
2 | Malignant neoplasms(C00–C97) | 415 | 17.1 | 121.9
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 237 | 9.7 | 69.6
4 | Diabetes mellitus(E10–E14) | 150 | 6.2 | 44.1
5 | Cerebrovascular diseases(I60–I69) | 130 | 5.3 | 38.2
6 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 79 | 3.2 | 23.2
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 75 | 3.1 | 22.0
8 | Chronic lower respiratory diseases(J40–J47) | 54 | 2.2 | 15.9
9 | Influenza and pneumonia(J09–J18) | 39 | 1.6 | 11.5
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 35 | 1.4 | 10.3
… | All other causes(residual) | 610 | 25.1 | 179.1
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 1–4
… | All causes | 11 | 100.0 | 60.5
1 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
3 | Septicemia(A40–A41) | §§ | §§ | §§
3 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 5–9
… | All causes | §§ | §§ | §§
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Septicemia(A40–A41) | §§ | §§ | §§
2 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 10–14
… | All causes | §§ | §§ | §§
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
2 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 15–19
… | All causes | 20 | 100.0 | 83.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
3 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
6 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
6 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 20–24
… | All causes | 47 | 100.0 | 192.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 17 | 36.2 | 69.5
2 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 10 | 21.3 | 40.9
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
5 | Pneumonitis due to solids and liquids(J69) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 25–34
… | All causes | 143 | 100.0 | 276.8
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 49 | 34.3 | 94.8
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 26 | 18.2 | 50.3
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 16 | 11.2 | 31.0
4 | Malignant neoplasms(C00–C97) | 14 | 9.8 | 27.1
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
6 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
7 | Septicemia(A40–A41) | §§ | §§ | §§
7 | Viral hepatitis(B15–B19) | §§ | §§ | §§
7 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
7 | Human immunodeficiency virus (HIV) disease(B20–B24) | §§ | §§ | §§
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | §§ | §§ | §§
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
7 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
7 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
7 | Meningitis(G00,G03) | §§ | §§ | §§
… | All other causes(residual) | 16 | 11.2 | 31.0
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 35–44
… | All causes | 240 | 100.0 | 437.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 60 | 25.0 | 109.3
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 48 | 20.0 | 87.5
3 | Malignant neoplasms(C00–C97) | 25 | 10.4 | 45.5
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 22 | 9.2 | 40.1
5 | Diabetes mellitus(E10–E14) | 14 | 5.8 | 25.5
6 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
7 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
8 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
… | All other causes(residual) | 48 | 20.0 | 87.5
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 45–54
… | All causes | 323 | 100.0 | 779.1
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 87 | 26.9 | 209.9
2 | Malignant neoplasms(C00–C97) | 58 | 18.0 | 139.9
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 30 | 9.3 | 72.4
4 | Diabetes mellitus(E10–E14) | 24 | 7.4 | 57.9
5 | Cerebrovascular diseases(I60–I69) | 20 | 6.2 | 48.2
6 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | §§ | §§ | §§
7 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
7 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
10 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
… | All other causes(residual) | 66 | 20.4 | 159.2
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 55–64
… | All causes | 444 | 100.0 | 1,266.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 130 | 29.3 | 370.8
2 | Malignant neoplasms(C00–C97) | 96 | 21.6 | 273.8
3 | Diabetes mellitus(E10–E14) | 36 | 8.1 | 102.7
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 35 | 7.9 | 99.8
5 | Cerebrovascular diseases(I60–I69) | 24 | 5.4 | 68.5
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 20 | 4.5 | 57.0
7 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 10 | 2.3 | 28.5
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
9 | Septicemia(A40–A41) | §§ | §§ | §§
9 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
… | All other causes(residual) | 68 | 15.3 | 194.0
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 65 and older
… | All causes | 1,143 | 100.0 | 2,966.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 322 | 28.2 | 835.7
2 | Malignant neoplasms(C00–C97) | 216 | 18.9 | 560.6
3 | Cerebrovascular diseases(I60–I69) | 79 | 6.9 | 205.0
4 | Diabetes mellitus(E10–E14) | 72 | 6.3 | 186.9
5 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 44 | 3.8 | 114.2
6 | Chronic lower respiratory diseases(J40–J47) | 43 | 3.8 | 111.6
7 | Alzheimer disease(G30) | 30 | 2.6 | 77.9
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 29 | 2.5 | 75.3
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 19 | 1.7 | 49.3
10 | Influenza and pneumonia(J09–J18) | 17 | 1.5 | 44.1
… | All other causes(residual) | 272 | 23.8 | 705.9
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 65–74
… | All causes | 518 | 100.0 | 2,141.6
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 147 | 28.4 | 607.8
2 | Malignant neoplasms(C00–C97) | 109 | 21.0 | 450.7
3 | Cerebrovascular diseases(I60–I69) | 45 | 8.7 | 186.1
4 | Diabetes mellitus(E10–E14) | 41 | 7.9 | 169.5
5 | Chronic lower respiratory diseases(J40–J47) | 20 | 3.9 | 82.7
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 17 | 3.3 | 70.3
7 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 15 | 2.9 | 62.0
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | §§ | §§ | §§
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
10 | COVID-19(*U07.1) | §§ | §§ | §§
10 | Nutritional deficiencies(E40–E64) | §§ | §§ | §§
10 | Parkinson disease(G20–G21) | §§ | §§ | §§
… | All other causes(residual) | 94 | 18.1 | 388.6
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 75–84
… | All causes | 455 | 100.0 | 4,086.9
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 131 | 28.8 | 1,176.7
2 | Malignant neoplasms(C00–C97) | 88 | 19.3 | 790.4
3 | Cerebrovascular diseases(I60–I69) | 24 | 5.3 | 215.6
4 | Diabetes mellitus(E10–E14) | 23 | 5.1 | 206.6
4 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 23 | 5.1 | 206.6
6 | Chronic lower respiratory diseases(J40–J47) | 15 | 3.3 | 134.7
7 | Alzheimer disease(G30) | 13 | 2.9 | 116.8
8 | Influenza and pneumonia(J09–J18) | 10 | 2.2 | 89.8
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 10 | 2.2 | 89.8
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 110 | 24.2 | 988.1
| Native Hawaiian and Other Pacific Islander, non-Hispanic, male, 85 and older
… | All causes | 170 | 100.0 | 5,292.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 44 | 25.9 | 1,369.9
2 | Malignant neoplasms(C00–C97) | 19 | 11.2 | 591.5
3 | Alzheimer disease(G30) | 13 | 7.6 | 404.7
4 | Cerebrovascular diseases(I60–I69) | 10 | 5.9 | 311.3
5 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
5 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | §§ | §§ | §§
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
8 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
8 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 47 | 27.6 | 1,463.3
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, all ages^††^
… | All causes | 2,000 | 100.0 | 598.2
1 | Malignant neoplasms(C00–C97) | 498 | 24.9 | 149.0
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 428 | 21.4 | 128.0
3 | Diabetes mellitus(E10–E14) | 145 | 7.3 | 43.4
4 | Cerebrovascular diseases(I60–I69) | 137 | 6.9 | 41.0
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 72 | 3.6 | 21.5
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 67 | 3.4 | 20.0
7 | Alzheimer disease(G30) | 50 | 2.5 | 15.0
8 | Chronic lower respiratory diseases(J40–J47) | 44 | 2.2 | 13.2
9 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 43 | 2.2 | 12.9
10 | Influenza and pneumonia(J09–J18) | 38 | 1.9 | 11.4
… | All other causes(residual) | 478 | 23.9 | 143.0
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 1–4
… | All causes | §§ | §§ | §§
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
1 | Aortic aneurysm and dissection(I71) | §§ | §§ | §§
1 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 5–9
… | All causes | §§ | §§ | §§
1 | Acute bronchitis and bronchiolitis(J20–J21) | §§ | §§ | §§
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 10–14
… | All causes | §§ | §§ | §§
1 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
… | All other causes(residual) | 0 | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 15–19
… | All causes | §§ | §§ | §§
1 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
2 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Legal intervention(Y35,Y89.0) | §§ | §§ | §§
… | All other causes(residual) | 0 | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 20–24
… | All causes | 14 | 100.0 | 59.5
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
3 | Tuberculosis(A16–A19) | §§ | §§ | §§
3 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
3 | Pregnancy, childbirth and the puerperium(O00–O99) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 25–34
… | All causes | 59 | 100.0 | 118.7
1 | Malignant neoplasms(C00–C97) | 13 | 22.0 | 26.2
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 10 | 16.9 | 20.1
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | §§ | §§ | §§
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | §§ | §§ | §§
6 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
6 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
8 | Tuberculosis(A16–A19) | §§ | §§ | §§
8 | Septicemia(A40–A41) | §§ | §§ | §§
8 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | Pregnancy, childbirth and the puerperium(O00–O99) | §§ | §§ | §§
8 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 35–44
… | All causes | 126 | 100.0 | 243.1
1 | Malignant neoplasms(C00–C97) | 36 | 28.6 | 69.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 25 | 19.8 | 48.2
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 16 | 12.7 | 30.9
4 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | §§ | §§ | §§
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
8 | COVID-19(*U07.1) | §§ | §§ | §§
8 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
8 | Diabetes mellitus(E10–E14) | §§ | §§ | §§
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | §§ | §§ | §§
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
… | All other causes(residual) | 23 | 18.3 | 44.4
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 45–54
… | All causes | 236 | 100.0 | 590.8
1 | Malignant neoplasms(C00–C97) | 72 | 30.5 | 180.2
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 46 | 19.5 | 115.2
3 | Diabetes mellitus(E10–E14) | 19 | 8.1 | 47.6
4 | Cerebrovascular diseases(I60–I69) | 16 | 6.8 | 40.1
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 12 | 5.1 | 30.0
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 11 | 4.7 | 27.5
7 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | Septicemia(A40–A41) | §§ | §§ | §§
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | §§ | §§ | §§
10 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
10 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
… | All other causes(residual) | 38 | 16.1 | 95.1
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 55–64
… | All causes | 401 | 100.0 | 1,109.1
1 | Malignant neoplasms(C00–C97) | 147 | 36.7 | 406.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 73 | 18.2 | 201.9
3 | Diabetes mellitus(E10–E14) | 34 | 8.5 | 94.0
4 | Cerebrovascular diseases(I60–I69) | 24 | 6.0 | 66.4
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 12 | 3.0 | 33.2
6 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | §§ | §§ | §§
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | §§ | §§ | §§
9 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
10 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
… | All other causes(residual) | 78 | 19.5 | 215.7
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 65 and older
… | All causes | 1,117 | 100.0 | 2,565.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 274 | 24.5 | 629.3
2 | Malignant neoplasms(C00–C97) | 227 | 20.3 | 521.4
3 | Cerebrovascular diseases(I60–I69) | 92 | 8.2 | 211.3
4 | Diabetes mellitus(E10–E14) | 88 | 7.9 | 202.1
5 | Alzheimer disease(G30) | 49 | 4.4 | 112.5
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 44 | 3.9 | 101.1
7 | Chronic lower respiratory diseases(J40–J47) | 32 | 2.9 | 73.5
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 28 | 2.5 | 64.3
9 | Septicemia(A40–A41) | 21 | 1.9 | 48.2
10 | Influenza and pneumonia(J09–J18) | 20 | 1.8 | 45.9
… | All other causes(residual) | 242 | 21.7 | 555.8
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 65–74
… | All causes | 472 | 100.0 | 1,804.4
1 | Malignant neoplasms(C00–C97) | 127 | 26.9 | 485.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 107 | 22.7 | 409.0
3 | Diabetes mellitus(E10–E14) | 52 | 11.0 | 198.8
4 | Cerebrovascular diseases(I60–I69) | 29 | 6.1 | 110.9
5 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 22 | 4.7 | 84.1
6 | Chronic lower respiratory diseases(J40–J47) | 14 | 3.0 | 53.5
7 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 12 | 2.5 | 45.9
8 | Septicemia(A40–A41) | §§ | §§ | §§
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
10 | Alzheimer disease(G30) | §§ | §§ | §§
10 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 79 | 16.7 | 302.0
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 75–84
… | All causes | 385 | 100.0 | 2,997.7
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 107 | 27.8 | 833.1
2 | Malignant neoplasms(C00–C97) | 73 | 19.0 | 568.4
3 | Cerebrovascular diseases(I60–I69) | 29 | 7.5 | 225.8
4 | Diabetes mellitus(E10–E14) | 21 | 5.5 | 163.5
5 | Chronic lower respiratory diseases(J40–J47) | 15 | 3.9 | 116.8
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 14 | 3.6 | 109.0
7 | Alzheimer disease(G30) | 12 | 3.1 | 93.4
8 | Septicemia(A40–A41) | 10 | 2.6 | 77.9
8 | Influenza and pneumonia(J09–J18) | 10 | 2.6 | 77.9
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | §§ | §§ | §§
… | All other causes(residual) | 86 | 22.3 | 669.6
| Native Hawaiian and Other Pacific Islander, non-Hispanic, female, 85 and older
… | All causes | 260 | 100.0 | 5,729.4
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 60 | 23.1 | 1,322.2
2 | Cerebrovascular diseases(I60–I69) | 34 | 13.1 | 749.2
3 | Alzheimer disease(G30) | 30 | 11.5 | 661.1
4 | Malignant neoplasms(C00–C97) | 27 | 10.4 | 595.0
5 | Diabetes mellitus(E10–E14) | 15 | 5.8 | 330.5
6 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | §§ | §§ | §§
6 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | §§ | §§ | §§
8 | Nutritional deficiencies(E40–E64) | §§ | §§ | §§
9 | Pneumonitis due to solids and liquids(J69) | §§ | §§ | §§
10 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
10 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
10 | Parkinson disease(G20–G21) | §§ | §§ | §§
10 | Aortic aneurysm and dissection(I71) | §§ | §§ | §§
… | All other causes(residual) | 54 | 20.8 | 1,190.0
| White, non-Hispanic, both sexes, all ages^††^
… | All causes | 2,290,348 | 100.0 | 1,171.9
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 520,559 | 22.7 | 266.4
2 | Malignant neoplasms(C00–C97) | 466,773 | 20.4 | 238.8
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 132,227 | 5.8 | 67.7
4 | Chronic lower respiratory diseases(J40–J47) | 124,575 | 5.4 | 63.7
5 | Cerebrovascular diseases(I60–I69) | 120,457 | 5.3 | 61.6
6 | Alzheimer disease(G30) | 93,490 | 4.1 | 47.8
7 | Diabetes mellitus(E10–E14) | 59,490 | 2.6 | 30.4
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | 37,036 | 1.6 | 19.0
9 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 36,560 | 1.6 | 18.7
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 36,364 | 1.6 | 18.6
… | All other causes(residual) | 662,817 | 28.9 | 339.2
| White, non-Hispanic, both sexes, 1–4
… | All causes | 1,484 | 100.0 | 21.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 518 | 34.9 | 7.6
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 170 | 11.5 | 2.5
3 | Malignant neoplasms(C00–C97) | 119 | 8.0 | 1.7
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 69 | 4.6 | 1.0
5 | Influenza and pneumonia(J09–J18) | 50 | 3.4 | 0.7
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 40 | 2.7 | 0.6
7 | Certain conditions originating in the perinatal period(P00–P96) | 22 | 1.5 | 0.3
8 | Septicemia(A40–A41) | 21 | 1.4 | 0.3
9 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 17 | 1.1 | 0.2
9 | COVID-19(*U07.1) | 17 | 1.1 | 0.2
… | All other causes(residual) | 441 | 29.7 | 6.4
| White, non-Hispanic, both sexes, 5–9
… | All causes | 1,036 | 100.0 | 10.8
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 324 | 31.3 | 3.4
2 | Malignant neoplasms(C00–C97) | 176 | 17.0 | 1.8
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 102 | 9.8 | 1.1
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 40 | 3.9 | 0.4
5 | Influenza and pneumonia(J09–J18) | 36 | 3.5 | 0.4
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 31 | 3.0 | 0.3
7 | Cerebrovascular diseases(I60–I69) | 22 | 2.1 | 0.2
8 | Septicemia(A40–A41) | 18 | 1.7 | 0.2
9 | Chronic lower respiratory diseases(J40–J47) | 12 | 1.2 | 0.1
10 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 10 | 1.0 | 0.1
… | All other causes(residual) | 265 | 25.6 | 2.8
| White, non-Hispanic, both sexes, 10–14
… | All causes | 1,524 | 100.0 | 15.1
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 383 | 25.1 | 3.8
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 282 | 18.5 | 2.8
3 | Malignant neoplasms(C00–C97) | 215 | 14.1 | 2.1
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 92 | 6.0 | 0.9
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 59 | 3.9 | 0.6
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 46 | 3.0 | 0.5
7 | Influenza and pneumonia(J09–J18) | 28 | 1.8 | 0.3
8 | Cerebrovascular diseases(I60–I69) | 25 | 1.6 | 0.2
9 | Septicemia(A40–A41) | 19 | 1.2 | 0.2
10 | Chronic lower respiratory diseases(J40–J47) | 17 | 1.1 | 0.2
… | All other causes(residual) | 358 | 23.5 | 3.5
| White, non-Hispanic, both sexes, 15–19
… | All causes | 4,808 | 100.0 | 43.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 2,095 | 43.6 | 19.1
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,170 | 24.3 | 10.6
3 | Malignant neoplasms(C00–C97) | 272 | 5.7 | 2.5
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 242 | 5.0 | 2.2
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 135 | 2.8 | 1.2
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 113 | 2.4 | 1.0
7 | Diabetes mellitus(E10–E14) | 38 | 0.8 | 0.3
8 | Influenza and pneumonia(J09–J18) | 36 | 0.7 | 0.3
9 | Cerebrovascular diseases(I60–I69) | 24 | 0.5 | 0.2
10 | Chronic lower respiratory diseases(J40–J47) | 22 | 0.5 | 0.2
… | All other causes(residual) | 661 | 13.7 | 6.0
| White, non-Hispanic, both sexes, 20–24
… | All causes | 7,878 | 100.0 | 69.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3,484 | 44.2 | 30.6
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 2,004 | 25.4 | 17.6
3 | Malignant neoplasms(C00–C97) | 375 | 4.8 | 3.3
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 318 | 4.0 | 2.8
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 228 | 2.9 | 2.0
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 141 | 1.8 | 1.2
7 | Diabetes mellitus(E10–E14) | 91 | 1.2 | 0.8
8 | Influenza and pneumonia(J09–J18) | 49 | 0.6 | 0.4
9 | Chronic lower respiratory diseases(J40–J47) | 44 | 0.6 | 0.4
10 | Pregnancy, childbirth and the puerperium(O00–O99) | 43 | 0.5 | 0.4
10 | Cerebrovascular diseases(I60–I69) | 43 | 0.5 | 0.4
… | All other causes(residual) | 1,058 | 13.4 | 9.3
| White, non-Hispanic, both sexes, 25–34
… | All causes | 28,020 | 100.0 | 116.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 11,970 | 42.7 | 49.7
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 4,904 | 17.5 | 20.3
3 | Malignant neoplasms(C00–C97) | 1,836 | 6.6 | 7.6
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,587 | 5.7 | 6.6
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 835 | 3.0 | 3.5
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 802 | 2.9 | 3.3
7 | Diabetes mellitus(E10–E14) | 460 | 1.6 | 1.9
8 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 272 | 1.0 | 1.1
9 | Influenza and pneumonia(J09–J18) | 219 | 0.8 | 0.9
10 | Cerebrovascular diseases(I60–I69) | 205 | 0.7 | 0.9
… | All other causes(residual) | 4,930 | 17.6 | 20.5
| White, non-Hispanic, both sexes, 35–44
… | All causes | 54,416 | 100.0 | 217.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 17,409 | 32.0 | 69.7
2 | Malignant neoplasms(C00–C97) | 6,523 | 12.0 | 26.1
3 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 6,132 | 11.3 | 24.6
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 5,884 | 10.8 | 23.6
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 3,058 | 5.6 | 12.2
6 | Diabetes mellitus(E10–E14) | 1,215 | 2.2 | 4.9
7 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 1,072 | 2.0 | 4.3
8 | Cerebrovascular diseases(I60–I69) | 881 | 1.6 | 3.5
9 | Influenza and pneumonia(J09–J18) | 559 | 1.0 | 2.2
10 | Septicemia(A40–A41) | 460 | 0.8 | 1.8
… | All other causes(residual) | 11,223 | 20.6 | 44.9
| White, non-Hispanic, both sexes, 45–54
… | All causes | 94,461 | 100.0 | 402.3
1 | Malignant neoplasms(C00–C97) | 20,037 | 21.2 | 85.3
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 17,095 | 18.1 | 72.8
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 15,536 | 16.4 | 66.2
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 6,042 | 6.4 | 25.7
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 5,378 | 5.7 | 22.9
6 | Diabetes mellitus(E10–E14) | 3,368 | 3.6 | 14.3
7 | Cerebrovascular diseases(I60–I69) | 2,414 | 2.6 | 10.3
8 | Chronic lower respiratory diseases(J40–J47) | 1,813 | 1.9 | 7.7
9 | Septicemia(A40–A41) | 1,204 | 1.3 | 5.1
10 | Influenza and pneumonia(J09–J18) | 1,130 | 1.2 | 4.8
… | All other causes(residual) | 20,444 | 21.6 | 87.1
| White, non-Hispanic, both sexes, 55–64
… | All causes | 242,715 | 100.0 | 890.4
1 | Malignant neoplasms(C00–C97) | 68,821 | 28.4 | 252.5
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 50,774 | 20.9 | 186.3
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 18,482 | 7.6 | 67.8
4 | Chronic lower respiratory diseases(J40–J47) | 12,588 | 5.2 | 46.2
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 10,268 | 4.2 | 37.7
6 | Diabetes mellitus(E10–E14) | 9,023 | 3.7 | 33.1
7 | Cerebrovascular diseases(I60–I69) | 7,554 | 3.1 | 27.7
8 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 6,575 | 2.7 | 24.1
9 | Septicemia(A40–A41) | 3,427 | 1.4 | 12.6
10 | Influenza and pneumonia(J09–J18) | 3,226 | 1.3 | 11.8
… | All other causes(residual) | 51,977 | 21.4 | 190.7
| White, non-Hispanic, both sexes, 65 and older
… | All causes | 1,846,321 | 100.0 | 4,099.3
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 444,635 | 24.1 | 987.2
2 | Malignant neoplasms(C00–C97) | 368,369 | 20.0 | 817.9
3 | Chronic lower respiratory diseases(J40–J47) | 109,561 | 5.9 | 243.3
4 | Cerebrovascular diseases(I60–I69) | 109,239 | 5.9 | 242.5
5 | Alzheimer disease(G30) | 92,309 | 5.0 | 204.9
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 61,532 | 3.3 | 136.6
7 | Diabetes mellitus(E10–E14) | 45,276 | 2.5 | 100.5
8 | Parkinson disease(G20–G21) | 34,056 | 1.8 | 75.6
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 31,718 | 1.7 | 70.4
10 | Influenza and pneumonia(J09–J18) | 29,728 | 1.6 | 66.0
… | All other causes(residual) | 519,898 | 28.2 | 1,154.3
| White, non-Hispanic, both sexes, 65–74
… | All causes | 460,732 | 100.0 | 1,805.6
1 | Malignant neoplasms(C00–C97) | 135,690 | 29.5 | 531.8
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 97,765 | 21.2 | 383.1
3 | Chronic lower respiratory diseases(J40–J47) | 33,036 | 7.2 | 129.5
4 | Cerebrovascular diseases(I60–I69) | 18,544 | 4.0 | 72.7
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 16,781 | 3.6 | 65.8
6 | Diabetes mellitus(E10–E14) | 15,510 | 3.4 | 60.8
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 10,110 | 2.2 | 39.6
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 7,356 | 1.6 | 28.8
9 | Alzheimer disease(G30) | 7,350 | 1.6 | 28.8
10 | Septicemia(A40–A41) | 6,796 | 1.5 | 26.6
… | All other causes(residual) | 111,794 | 24.3 | 438.1
| White, non-Hispanic, both sexes, 75–84
… | All causes | 656,112 | 100.0 | 4,473.8
1 | Malignant neoplasms(C00–C97) | 146,846 | 22.4 | 1,001.3
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 143,810 | 21.9 | 980.6
3 | Chronic lower respiratory diseases(J40–J47) | 44,870 | 6.8 | 306.0
4 | Cerebrovascular diseases(I60–I69) | 36,767 | 5.6 | 250.7
5 | Alzheimer disease(G30) | 30,705 | 4.7 | 209.4
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 20,168 | 3.1 | 137.5
7 | Diabetes mellitus(E10–E14) | 17,710 | 2.7 | 120.8
8 | Parkinson disease(G20–G21) | 16,183 | 2.5 | 110.3
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 11,919 | 1.8 | 81.3
10 | Influenza and pneumonia(J09–J18) | 10,313 | 1.6 | 70.3
… | All other causes(residual) | 176,821 | 26.9 | 1,205.7
| White, non-Hispanic, both sexes, 85 and older
… | All causes | 729,477 | 100.0 | 15,018.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 203,060 | 27.8 | 4,180.6
2 | Malignant neoplasms(C00–C97) | 85,833 | 11.8 | 1,767.1
3 | Alzheimer disease(G30) | 54,254 | 7.4 | 1,117.0
4 | Cerebrovascular diseases(I60–I69) | 53,928 | 7.4 | 1,110.3
5 | Chronic lower respiratory diseases(J40–J47) | 31,655 | 4.3 | 651.7
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 24,583 | 3.4 | 506.1
7 | Influenza and pneumonia(J09–J18) | 12,764 | 1.7 | 262.8
8 | Parkinson disease(G20–G21) | 12,455 | 1.7 | 256.4
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 12,443 | 1.7 | 256.2
10 | Diabetes mellitus(E10–E14) | 12,056 | 1.7 | 248.2
… | All other causes(residual) | 226,446 | 31.0 | 4,662.1
| White, non-Hispanic, male, all ages^††^
… | All causes | 1,177,767 | 100.0 | 1,215.1
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 285,856 | 24.3 | 294.9
2 | Malignant neoplasms(C00–C97) | 248,591 | 21.1 | 256.5
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 82,665 | 7.0 | 85.3
4 | Chronic lower respiratory diseases(J40–J47) | 57,146 | 4.9 | 59.0
5 | Cerebrovascular diseases(I60–I69) | 51,838 | 4.4 | 53.5
6 | Diabetes mellitus(E10–E14) | 34,984 | 3.0 | 36.1
7 | Alzheimer disease(G30) | 30,321 | 2.6 | 31.3
8 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 29,288 | 2.5 | 30.2
9 | Chronic liver disease and cirrhosis(K70,K73–K74) | 22,436 | 1.9 | 23.1
10 | Parkinson disease(G20–G21) | 21,684 | 1.8 | 22.4
… | All other causes(residual) | 312,958 | 26.6 | 322.9
| White, non-Hispanic, male, 1–4
… | All causes | 863 | 100.0 | 24.5
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 316 | 36.6 | 9.0
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 92 | 10.7 | 2.6
3 | Malignant neoplasms(C00–C97) | 60 | 7.0 | 1.7
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 39 | 4.5 | 1.1
5 | Influenza and pneumonia(J09–J18) | 33 | 3.8 | 0.9
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 19 | 2.2 | 0.5
7 | Certain conditions originating in the perinatal period(P00–P96) | 15 | 1.7 | 0.4
8 | Septicemia(A40–A41) | 12 | 1.4 | 0.3
9 | COVID-19(*U07.1) | 11 | 1.3 | 0.3
10 | Cerebrovascular diseases(I60–I69) | 10 | 1.2 | 0.3
… | All other causes(residual) | 256 | 29.7 | 7.3
| White, non-Hispanic, male, 5–9
… | All causes | 525 | 100.0 | 10.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 171 | 32.6 | 3.5
2 | Malignant neoplasms(C00–C97) | 87 | 16.6 | 1.8
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 54 | 10.3 | 1.1
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 21 | 4.0 | 0.4
5 | Influenza and pneumonia(J09–J18) | 20 | 3.8 | 0.4
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 18 | 3.4 | 0.4
7 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
8 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
8 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 122 | 23.2 | 2.5
| White, non-Hispanic, male, 10–14
… | All causes | 878 | 100.0 | 16.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 260 | 29.6 | 5.0
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 149 | 17.0 | 2.9
3 | Malignant neoplasms(C00–C97) | 116 | 13.2 | 2.2
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 63 | 7.2 | 1.2
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 40 | 4.6 | 0.8
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 25 | 2.8 | 0.5
7 | Influenza and pneumonia(J09–J18) | 14 | 1.6 | 0.3
8 | Cerebrovascular diseases(I60–I69) | 13 | 1.5 | 0.3
9 | Chronic lower respiratory diseases(J40–J47) | 11 | 1.3 | 0.2
10 | Septicemia(A40–A41) | 10 | 1.1 | 0.2
… | All other causes(residual) | 177 | 20.2 | 3.4
| White, non-Hispanic, male, 15–19
… | All causes | 3,342 | 100.0 | 59.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 1,513 | 45.3 | 26.8
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 888 | 26.6 | 15.7
3 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 187 | 5.6 | 3.3
4 | Malignant neoplasms(C00–C97) | 162 | 4.8 | 2.9
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 90 | 2.7 | 1.6
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 60 | 1.8 | 1.1
7 | Diabetes mellitus(E10–E14) | 27 | 0.8 | 0.5
8 | Influenza and pneumonia(J09–J18) | 21 | 0.6 | 0.4
9 | Legal intervention(Y35,Y89.0) | 15 | 0.4 | 0.3
10 | Chronic lower respiratory diseases(J40–J47) | 11 | 0.3 | 0.2
… | All other causes(residual) | 368 | 11.0 | 6.5
| White, non-Hispanic, male, 20–24
… | All causes | 5,676 | 100.0 | 97.2
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 2,583 | 45.5 | 44.2
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,652 | 29.1 | 28.3
3 | Malignant neoplasms(C00–C97) | 234 | 4.1 | 4.0
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 213 | 3.8 | 3.6
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 151 | 2.7 | 2.6
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 74 | 1.3 | 1.3
7 | Diabetes mellitus(E10–E14) | 64 | 1.1 | 1.1
8 | Cerebrovascular diseases(I60–I69) | 29 | 0.5 | 0.5
9 | Influenza and pneumonia(J09–J18) | 28 | 0.5 | 0.5
10 | Chronic lower respiratory diseases(J40–J47) | 23 | 0.4 | 0.4
… | All other causes(residual) | 625 | 11.0 | 10.7
| White, non-Hispanic, male, 25–34
… | All causes | 19,307 | 100.0 | 157.5
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 8,581 | 44.4 | 70.0
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 3,967 | 20.5 | 32.4
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,058 | 5.5 | 8.6
4 | Malignant neoplasms(C00–C97) | 902 | 4.7 | 7.4
5 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 577 | 3.0 | 4.7
6 | Chronic liver disease and cirrhosis(K70,K73–K74) | 513 | 2.7 | 4.2
7 | Diabetes mellitus(E10–E14) | 311 | 1.6 | 2.5
8 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 160 | 0.8 | 1.3
9 | Influenza and pneumonia(J09–J18) | 134 | 0.7 | 1.1
10 | Cerebrovascular diseases(I60–I69) | 125 | 0.6 | 1.0
… | All other causes(residual) | 2,979 | 15.4 | 24.3
| White, non-Hispanic, male, 35–44
… | All causes | 35,290 | 100.0 | 279.3
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 12,297 | 34.8 | 97.3
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 4,876 | 13.8 | 38.6
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 3,997 | 11.3 | 31.6
4 | Malignant neoplasms(C00–C97) | 2,967 | 8.4 | 23.5
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,875 | 5.3 | 14.8
6 | Diabetes mellitus(E10–E14) | 773 | 2.2 | 6.1
7 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 760 | 2.2 | 6.0
8 | Cerebrovascular diseases(I60–I69) | 485 | 1.4 | 3.8
9 | Influenza and pneumonia(J09–J18) | 299 | 0.8 | 2.4
10 | Septicemia(A40–A41) | 244 | 0.7 | 1.9
… | All other causes(residual) | 6,717 | 19.0 | 53.2
| White, non-Hispanic, male, 45–54
… | All causes | 58,545 | 100.0 | 493.8
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 12,117 | 20.7 | 102.2
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 10,776 | 18.4 | 90.9
3 | Malignant neoplasms(C00–C97) | 9,944 | 17.0 | 83.9
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 4,674 | 8.0 | 39.4
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 3,326 | 5.7 | 28.1
6 | Diabetes mellitus(E10–E14) | 2,202 | 3.8 | 18.6
7 | Cerebrovascular diseases(I60–I69) | 1,390 | 2.4 | 11.7
8 | Chronic lower respiratory diseases(J40–J47) | 824 | 1.4 | 6.9
9 | Septicemia(A40–A41) | 611 | 1.0 | 5.2
10 | Influenza and pneumonia(J09–J18) | 602 | 1.0 | 5.1
… | All other causes(residual) | 12,079 | 20.6 | 101.9
| White, non-Hispanic, male, 55–64
… | All causes | 147,267 | 100.0 | 1,089.7
1 | Malignant neoplasms(C00–C97) | 36,897 | 25.1 | 273.0
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 35,684 | 24.2 | 264.1
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 12,957 | 8.8 | 95.9
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 6,369 | 4.3 | 47.1
5 | Chronic lower respiratory diseases(J40–J47) | 6,071 | 4.1 | 44.9
6 | Diabetes mellitus(E10–E14) | 5,908 | 4.0 | 43.7
7 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 5,160 | 3.5 | 38.2
8 | Cerebrovascular diseases(I60–I69) | 4,448 | 3.0 | 32.9
9 | Septicemia(A40–A41) | 1,852 | 1.3 | 13.7
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 1,769 | 1.2 | 13.1
… | All other causes(residual) | 30,152 | 20.5 | 223.1
| White, non-Hispanic, male, 65 and older
… | All causes | 901,901 | 100.0 | 4,356.3
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 232,636 | 25.8 | 1,123.7
2 | Malignant neoplasms(C00–C97) | 197,208 | 21.9 | 952.5
3 | Chronic lower respiratory diseases(J40–J47) | 49,966 | 5.5 | 241.3
4 | Cerebrovascular diseases(I60–I69) | 45,303 | 5.0 | 218.8
5 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 32,937 | 3.7 | 159.1
6 | Alzheimer disease(G30) | 29,800 | 3.3 | 143.9
7 | Diabetes mellitus(E10–E14) | 25,694 | 2.8 | 124.1
8 | Parkinson disease(G20–G21) | 21,212 | 2.4 | 102.5
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 16,376 | 1.8 | 79.1
10 | Influenza and pneumonia(J09–J18) | 14,860 | 1.6 | 71.8
… | All other causes(residual) | 235,909 | 26.2 | 1,139.5
| White, non-Hispanic, male, 65–74
… | All causes | 265,855 | 100.0 | 2,175.7
1 | Malignant neoplasms(C00–C97) | 75,099 | 28.2 | 614.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 63,947 | 24.1 | 523.3
3 | Chronic lower respiratory diseases(J40–J47) | 16,538 | 6.2 | 135.3
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 11,136 | 4.2 | 91.1
5 | Cerebrovascular diseases(I60–I69) | 10,018 | 3.8 | 82.0
6 | Diabetes mellitus(E10–E14) | 9,621 | 3.6 | 78.7
7 | Chronic liver disease and cirrhosis(K70,K73–K74) | 6,258 | 2.4 | 51.2
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 4,140 | 1.6 | 33.9
9 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 3,868 | 1.5 | 31.7
10 | Influenza and pneumonia(J09–J18) | 3,653 | 1.4 | 29.9
… | All other causes(residual) | 61,577 | 23.2 | 503.9
| White, non-Hispanic, male, 75–84
… | All causes | 342,083 | 100.0 | 5,152.3
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 82,113 | 24.0 | 1,236.8
2 | Malignant neoplasms(C00–C97) | 79,414 | 23.2 | 1,196.1
3 | Chronic lower respiratory diseases(J40–J47) | 21,014 | 6.1 | 316.5
4 | Cerebrovascular diseases(I60–I69) | 16,952 | 5.0 | 255.3
5 | Alzheimer disease(G30) | 11,364 | 3.3 | 171.2
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 11,360 | 3.3 | 171.1
7 | Parkinson disease(G20–G21) | 10,523 | 3.1 | 158.5
8 | Diabetes mellitus(E10–E14) | 10,291 | 3.0 | 155.0
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 6,315 | 1.8 | 95.1
10 | Influenza and pneumonia(J09–J18) | 5,468 | 1.6 | 82.4
… | All other causes(residual) | 87,269 | 25.5 | 1,314.4
| White, non-Hispanic, male, 85 and older
… | All causes | 293,963 | 100.0 | 15,935.3
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 86,576 | 29.5 | 4,693.2
2 | Malignant neoplasms(C00–C97) | 42,695 | 14.5 | 2,314.4
3 | Cerebrovascular diseases(I60–I69) | 18,333 | 6.2 | 993.8
4 | Alzheimer disease(G30) | 15,479 | 5.3 | 839.1
5 | Chronic lower respiratory diseases(J40–J47) | 12,414 | 4.2 | 672.9
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 10,441 | 3.6 | 566.0
7 | Parkinson disease(G20–G21) | 7,130 | 2.4 | 386.5
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 5,921 | 2.0 | 321.0
9 | Diabetes mellitus(E10–E14) | 5,782 | 2.0 | 313.4
10 | Influenza and pneumonia(J09–J18) | 5,739 | 2.0 | 311.1
… | All other causes(residual) | 83,453 | 28.4 | 4,523.9
| White, non-Hispanic, female, all ages^††^
… | All causes | 1,112,581 | 100.0 | 1,129.5
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 234,703 | 21.1 | 238.3
2 | Malignant neoplasms(C00–C97) | 218,182 | 19.6 | 221.5
3 | Cerebrovascular diseases(I60–I69) | 68,619 | 6.2 | 69.7
4 | Chronic lower respiratory diseases(J40–J47) | 67,429 | 6.1 | 68.5
5 | Alzheimer disease(G30) | 63,169 | 5.7 | 64.1
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 49,562 | 4.5 | 50.3
7 | Diabetes mellitus(E10–E14) | 24,506 | 2.2 | 24.9
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 17,314 | 1.6 | 17.6
9 | Influenza and pneumonia(J09–J18) | 17,303 | 1.6 | 17.6
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 15,329 | 1.4 | 15.6
… | All other causes(residual) | 336,465 | 30.2 | 341.6
| White, non-Hispanic, female, 1–4
… | All causes | 621 | 100.0 | 18.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 202 | 32.5 | 6.0
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 78 | 12.6 | 2.3
3 | Malignant neoplasms(C00–C97) | 59 | 9.5 | 1.8
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 30 | 4.8 | 0.9
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 21 | 3.4 | 0.6
6 | Influenza and pneumonia(J09–J18) | 17 | 2.7 | 0.5
7 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 11 | 1.8 | 0.3
8 | Septicemia(A40–A41) | §§ | §§ | §§
9 | Certain conditions originating in the perinatal period(P00–P96) | §§ | §§ | §§
10 | Cerebrovascular diseases(I60–I69) | §§ | §§ | §§
10 | COVID-19(*U07.1) | §§ | §§ | §§
… | All other causes(residual) | 175 | 28.2 | 5.2
| White, non-Hispanic, female, 5–9
… | All causes | 511 | 100.0 | 10.9
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 153 | 29.9 | 3.3
2 | Malignant neoplasms(C00–C97) | 89 | 17.4 | 1.9
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 48 | 9.4 | 1.0
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 19 | 3.7 | 0.4
5 | Influenza and pneumonia(J09–J18) | 16 | 3.1 | 0.3
6 | Cerebrovascular diseases(I60–I69) | 13 | 2.5 | 0.3
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 13 | 2.5 | 0.3
8 | Septicemia(A40–A41) | 11 | 2.2 | 0.2
9 | Anemias(D50–D64) | §§ | §§ | §§
9 | Chronic lower respiratory diseases(J40–J47) | §§ | §§ | §§
… | All other causes(residual) | 141 | 27.6 | 3.0
| White, non-Hispanic, female, 10–14
… | All causes | 646 | 100.0 | 13.1
1 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 133 | 20.6 | 2.7
2 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 123 | 19.0 | 2.5
3 | Malignant neoplasms(C00–C97) | 99 | 15.3 | 2.0
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 29 | 4.5 | 0.6
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 21 | 3.3 | 0.4
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 19 | 2.9 | 0.4
7 | Influenza and pneumonia(J09–J18) | 14 | 2.2 | 0.3
8 | Cerebrovascular diseases(I60–I69) | 12 | 1.9 | 0.2
9 | Diabetes mellitus(E10–E14) | 11 | 1.7 | 0.2
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 176 | 27.2 | 3.6
| White, non-Hispanic, female, 15–19
… | All causes | 1,466 | 100.0 | 27.4
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 582 | 39.7 | 10.9
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 282 | 19.2 | 5.3
3 | Malignant neoplasms(C00–C97) | 110 | 7.5 | 2.1
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 55 | 3.8 | 1.0
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 53 | 3.6 | 1.0
6 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 45 | 3.1 | 0.8
7 | Influenza and pneumonia(J09–J18) | 15 | 1.0 | 0.3
7 | Cerebrovascular diseases(I60–I69) | 15 | 1.0 | 0.3
9 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 12 | 0.8 | 0.2
10 | Diabetes mellitus(E10–E14) | 11 | 0.8 | 0.2
10 | Chronic lower respiratory diseases(J40–J47) | 11 | 0.8 | 0.2
… | All other causes(residual) | 275 | 18.8 | 5.1
| White, non-Hispanic, female, 20–24
… | All causes | 2,202 | 100.0 | 39.7
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 901 | 40.9 | 16.2
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 352 | 16.0 | 6.3
3 | Malignant neoplasms(C00–C97) | 141 | 6.4 | 2.5
4 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 105 | 4.8 | 1.9
5 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 77 | 3.5 | 1.4
6 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 67 | 3.0 | 1.2
7 | Pregnancy, childbirth and the puerperium(O00–O99) | 43 | 2.0 | 0.8
8 | Diabetes mellitus(E10–E14) | 27 | 1.2 | 0.5
9 | Influenza and pneumonia(J09–J18) | 21 | 1.0 | 0.4
9 | Chronic lower respiratory diseases(J40–J47) | 21 | 1.0 | 0.4
… | All other causes(residual) | 447 | 20.3 | 8.1
| White, non-Hispanic, female, 25–34
… | All causes | 8,713 | 100.0 | 73.6
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3,389 | 38.9 | 28.6
2 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 937 | 10.8 | 7.9
3 | Malignant neoplasms(C00–C97) | 934 | 10.7 | 7.9
4 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 529 | 6.1 | 4.5
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 322 | 3.7 | 2.7
6 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 225 | 2.6 | 1.9
7 | Pregnancy, childbirth and the puerperium(O00–O99) | 202 | 2.3 | 1.7
8 | Diabetes mellitus(E10–E14) | 149 | 1.7 | 1.3
9 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 112 | 1.3 | 0.9
10 | Influenza and pneumonia(J09–J18) | 85 | 1.0 | 0.7
… | All other causes(residual) | 1,829 | 21.0 | 15.4
| White, non-Hispanic, female, 35–44
… | All causes | 19,126 | 100.0 | 155.0
1 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 5,112 | 26.7 | 41.4
2 | Malignant neoplasms(C00–C97) | 3,556 | 18.6 | 28.8
3 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 1,887 | 9.9 | 15.3
4 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,256 | 6.6 | 10.2
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 1,183 | 6.2 | 9.6
6 | Diabetes mellitus(E10–E14) | 442 | 2.3 | 3.6
7 | Cerebrovascular diseases(I60–I69) | 396 | 2.1 | 3.2
8 | Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 312 | 1.6 | 2.5
9 | Influenza and pneumonia(J09–J18) | 260 | 1.4 | 2.1
10 | Septicemia(A40–A41) | 216 | 1.1 | 1.8
… | All other causes(residual) | 4,506 | 23.6 | 36.5
| White, non-Hispanic, female, 45–54
… | All causes | 35,916 | 100.0 | 309.0
1 | Malignant neoplasms(C00–C97) | 10,093 | 28.1 | 86.8
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 4,978 | 13.9 | 42.8
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 4,760 | 13.3 | 41.0
4 | Chronic liver disease and cirrhosis(K70,K73–K74) | 2,052 | 5.7 | 17.7
5 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,368 | 3.8 | 11.8
6 | Diabetes mellitus(E10–E14) | 1,166 | 3.2 | 10.0
7 | Cerebrovascular diseases(I60–I69) | 1,024 | 2.9 | 8.8
8 | Chronic lower respiratory diseases(J40–J47) | 989 | 2.8 | 8.5
9 | Septicemia(A40–A41) | 593 | 1.7 | 5.1
10 | Influenza and pneumonia(J09–J18) | 528 | 1.5 | 4.5
… | All other causes(residual) | 8,365 | 23.3 | 72.0
| White, non-Hispanic, female, 55–64
… | All causes | 95,448 | 100.0 | 694.4
1 | Malignant neoplasms(C00–C97) | 31,924 | 33.4 | 232.3
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 15,090 | 15.8 | 109.8
3 | Chronic lower respiratory diseases(J40–J47) | 6,517 | 6.8 | 47.4
4 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 5,525 | 5.8 | 40.2
5 | Chronic liver disease and cirrhosis(K70,K73–K74) | 3,899 | 4.1 | 28.4
6 | Diabetes mellitus(E10–E14) | 3,115 | 3.3 | 22.7
7 | Cerebrovascular diseases(I60–I69) | 3,106 | 3.3 | 22.6
8 | Septicemia(A40–A41) | 1,575 | 1.7 | 11.5
9 | Influenza and pneumonia(J09–J18) | 1,466 | 1.5 | 10.7
10 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 1,415 | 1.5 | 10.3
… | All other causes(residual) | 21,816 | 22.9 | 158.7
| White, non-Hispanic, female, 65 and older
… | All causes | 944,420 | 100.0 | 3,880.6
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 211,999 | 22.4 | 871.1
2 | Malignant neoplasms(C00–C97) | 171,161 | 18.1 | 703.3
3 | Cerebrovascular diseases(I60–I69) | 63,936 | 6.8 | 262.7
4 | Alzheimer disease(G30) | 62,509 | 6.6 | 256.9
5 | Chronic lower respiratory diseases(J40–J47) | 59,595 | 6.3 | 244.9
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 28,595 | 3.0 | 117.5
7 | Diabetes mellitus(E10–E14) | 19,582 | 2.1 | 80.5
8 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 15,342 | 1.6 | 63.0
9 | Influenza and pneumonia(J09–J18) | 14,868 | 1.6 | 61.1
10 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 14,128 | 1.5 | 58.1
… | All other causes(residual) | 282,705 | 29.9 | 1,161.6
| White, non-Hispanic, female, 65–74
… | All causes | 194,877 | 100.0 | 1,465.5
1 | Malignant neoplasms(C00–C97) | 60,591 | 31.1 | 455.6
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 33,818 | 17.4 | 254.3
3 | Chronic lower respiratory diseases(J40–J47) | 16,498 | 8.5 | 124.1
4 | Cerebrovascular diseases(I60–I69) | 8,526 | 4.4 | 64.1
5 | Diabetes mellitus(E10–E14) | 5,889 | 3.0 | 44.3
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 5,645 | 2.9 | 42.4
7 | Alzheimer disease(G30) | 4,393 | 2.3 | 33.0
8 | Chronic liver disease and cirrhosis(K70,K73–K74) | 3,852 | 2.0 | 29.0
9 | Septicemia(A40–A41) | 3,259 | 1.7 | 24.5
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 3,216 | 1.7 | 24.2
… | All other causes(residual) | 49,190 | 25.2 | 369.9
| White, non-Hispanic, female, 75–84
… | All causes | 314,029 | 100.0 | 3,912.5
1 | Malignant neoplasms(C00–C97) | 67,432 | 21.5 | 840.1
2 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 61,697 | 19.6 | 768.7
3 | Chronic lower respiratory diseases(J40–J47) | 23,856 | 7.6 | 297.2
4 | Cerebrovascular diseases(I60–I69) | 19,815 | 6.3 | 246.9
5 | Alzheimer disease(G30) | 19,341 | 6.2 | 241.0
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 8,808 | 2.8 | 109.7
7 | Diabetes mellitus(E10–E14) | 7,419 | 2.4 | 92.4
8 | Parkinson disease(G20–G21) | 5,660 | 1.8 | 70.5
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 5,604 | 1.8 | 69.8
10 | Influenza and pneumonia(J09–J18) | 4,845 | 1.5 | 60.4
… | All other causes(residual) | 89,552 | 28.5 | 1,115.7
| White, non-Hispanic, female, 85 and older
… | All causes | 435,514 | 100.0 | 14,457.1
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 116,484 | 26.7 | 3,866.7
2 | Malignant neoplasms(C00–C97) | 43,138 | 9.9 | 1,432.0
3 | Alzheimer disease(G30) | 38,775 | 8.9 | 1,287.2
4 | Cerebrovascular diseases(I60–I69) | 35,595 | 8.2 | 1,181.6
5 | Chronic lower respiratory diseases(J40–J47) | 19,241 | 4.4 | 638.7
6 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 14,142 | 3.2 | 469.5
7 | Nutritional deficiencies(E40–E64) | 7,875 | 1.8 | 261.4
8 | Essential hypertension and hypertensive renal disease(I10,I12,I15) | 7,785 | 1.8 | 258.4
9 | Influenza and pneumonia(J09–J18) | 7,025 | 1.6 | 233.2
10 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 6,522 | 1.5 | 216.5
… | All other causes(residual) | 138,932 | 31.9 | 4,611.9

†Based on number of deaths.

§ Data for age not stated are included in "all ages" but not distributed among age groups.

¶ Data for two or more races and origin not stated are included in "all races and origins" but are not distributed among race and Hispanic-origin groups. For the race and Hispanic-origin categories shown, only one race was reported on the death certificate.

** Percentages may not add to 100 because of rounding.

†† Includes deaths for younger than 1 year.

… Category not applicable.

§§ Estimate does not meet National Center for Health statistics standards of reliability.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Selection of the 52 rankable causes was guided by some basic principles. As done previously, vaguely defined categories were excluded from selection as rankable causes. These included the category “Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified” and all categories beginning with the words “other,” “all other,” “certain other,” or “unspecified.” Among the remaining cause-of-death categories, decisions were made to select as rankable the causes of death considered most useful from a public health perspective, with the following condition: The rankable causes must be mutually exclusive. If a category containing subcategories (for example, Tuberculosis or Malignant neoplasms) is selected as a rankable cause, its component parts are not selected as rankable. Efforts were also made to maintain historical continuity where possible.

Beginning with 1980 mortality data, NCHS introduced a separate ranking procedure for infant causes of death using a specialized list of infant causes. This was done to include in the rankings those causes specific to infancy (especially the perinatal period—the period beginning shortly before and ending shortly after birth) that would otherwise be excluded. The ICD–10 “List of 130 Selected Causes of Infant Death” (8) (Table B) is used to select 71 rankable causes of infant death from which the rankings in Table 2 are derived. The same principles for selecting the rankable causes from the “List of 113 Selected Causes of Death” guided the selection of rankable causes from the infant cause list.

Table B List of 130 selected causes of infant death

[An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10)]

Number^†^ | Cause of death (based on ICD–10)
| Certain infectious and parasitic diseases(A00–B99,U07.1)
1 | Certain intestinal infectious diseases(A00–A08)
2# | Diarrhea and gastroenteritis of infectious origin(A09)
3# | Tuberculosis(A16–A19)
4# | Tetanus (A33,A35)
5# | Diphtheria(A36)
6# | Whooping cough(A37)
7# | Meningococcal infection(A39)
8# | Septicemia(A40–A41)
9# | Congenital syphilis(A50)
10# | Gonococcal infection(A54)
| Viral diseases(A80–B34)
11# | Acute poliomyelitis(A80)
12# | Varicella (chickenpox)(B01)
13# | Measles(B05)
14# | Human immunodeficiency virus (HIV) disease(B20–B24)
15# | Mumps(B26)
16 | Other and unspecified viral diseases(A81–B00,B02–B04,B06–B19,B25,B27–B34)
17# | Candidiasis(B37)
18# | Malaria(B50–B54)
19# | Pneumocystosis(B59)
20 | All other and unspecified infectious and parasitic diseases(A20–A32,A38,A42–A49,A51–A53,A55–A79,B35–B36,B38–B49,B55–B58,B60–B99,U07.1)
| Neoplasms(C00–D48)
# | Malignant neoplasms(C00–C97)
21 | Hodgkin disease and non–Hodgkin lymphomas(C81–C85)
22 | Leukemia(C91–C95)
23 | Other and unspecified malignant neoplasms(C00–C80,C88,C90,C96–C97)
24# | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48)
# | Diseases of the blood and blood–forming organs and certain disorders involving the immune mechanism(D50–D89)
25 | Anemias(D50–D64)
26 | Hemorrhagic conditions and other diseases of blood and blood–forming organs(D65–D76)
27 | Certain disorders involving the immune mechanism(D80–D89)
| Endocrine, nutritional and metabolic diseases(E00–E88)
28# | Short stature, not elsewhere classified(E34.3)
29# | Nutritional deficiencies(E40–E64)
30# | Cystic fibrosis(E84)
31# | Volume depletion, disorders of fluid, electrolyte and acid–base balance(E86–E87)
32 | All other endocrine, nutritional and metabolic diseases(E00–E32,E34.0–E34.2,E34.4–E34.9,E65–E83,E85,E88)
| Diseases of the nervous system(G00–G98)
33# | Meningitis(G00,G03)
34# | Infantile spinal muscular atrophy, type I (Werdnig–Hoffman)(G12.0)
35# | Infantile cerebral palsy(G80)
36# | Anoxic brain damage, not elsewhere classified(G93.1)
37 | Other diseases of nervous system(G04,G06–G11,G12.1–G12.9,G20–G72,G81–G92,G93.0,G93.2–G93.9,G95–G98)
38# | Diseases of the ear and mastoid process(H60–H93)
# | Diseases of the circulatory system(I00–I99)
39 | Pulmonary heart disease and diseases of pulmonary circulation(I26–I28)
40 | Pericarditis, endocarditis and myocarditis(I30,I33,I40)
41 | Cardiomyopathy(I42)
42 | Cardiac arrest(I46)
43 | Cerebrovascular diseases(I60–I69)
44 | All other diseases of circulatory system(I00–I25,I31,I34–I38,I44–I45,I47–I51,I70–I99)
| Diseases of the respiratory system(J00–J98,U04)
45# | Acute upper respiratory infections(J00–J06)
# | Influenza and pneumonia(J09–J18)
46 | Influenza(J09–J11)
47 | Pneumonia(J12–J18)
48# | Acute bronchitis and acute bronchiolitis(J20–J21)
49# | Bronchitis, chronic and unspecified(J40–J42)
50# | Asthma(J45–J46)
51# | Pneumonitis due to solids and liquids(J69)
52 | Other and unspecified diseases of respiratory system(J22,J30–J39,J43–J44,J47–J68,J70–J98,U04)
| Diseases of the digestive system(K00–K92)
53# | Gastritis, duodenitis, and noninfective enteritis and colitis(K29,K50–K55)
54# | Hernia of abdominal cavity and intestinal obstruction without hernia(K40–K46,K56)
55 | All other and unspecified diseases of digestive system(K00–K28,K30–K38,K57–K92)
| Diseases of the genitourinary system(N00–N95)
56# | Renal failure and other disorders of kidney(N17–N19,N25,N27)
57 | Other and unspecified diseases of genitourinary system(N00–N15,N20–N23,N26,N28–N95)
| Certain conditions originating in the perinatal period(P00–P96)
| Newborn affected by maternal factors and by complications of pregnancy, labor and delivery(P00–P04)
58# | Newborn affected by maternal hypertensive disorders(P00.0)
59# | Newborn affected by other maternal conditions which may be unrelated to present pregnancy(P00.1–P00.9)
# | Newborn affected by maternal complications of pregnancy(P01)
60 | Newborn affected by incompetent cervix(P01.0)
61 | Newborn affected by premature rupture of membranes(P01.1)
62 | Newborn affected by multiple pregnancy(P01.5)
63 | Newborn affected by other maternal complications of pregnancy(P01.2–P01.4,P01.6–P01.9)
# | Newborn affected by complications of placenta, cord and membranes(P02)
64 | Newborn affected by complications involving placenta(P02.0–P02.3)
65 | Newborn affected by complications involving cord(P02.4–P02.6)
66 | Newborn affected by chorioamnionitis(P02.7)
67 | Newborn affected by other and unspecified abnormalities of membranes(P02.8–P02.9)
68# | Newborn affected by other complications of labor and delivery(P03)
69# | Newborn affected by noxious influences transmitted via placenta or breast milk(P04)
| Disorders related to length of gestation and fetal malnutrition(P05–P08)
70# | Slow fetal growth and fetal malnutrition(P05)
# | Disorders related to short gestation and low birth weight, not elsewhere classified(P07)
71 | Extremely low birth weight or extreme immaturity(P07.0,P07.2)
72 | Other low birth weight or preterm(P07.1,P07.3)
73# | Disorders related to long gestation and high birth weight(P08)
74# | Birth trauma(P10–P15)
# | Intrauterine hypoxia and birth asphyxia(P20–P21)
75 | Intrauterine hypoxia(P20)
76 | Birth asphyxia(P21)
77# | Respiratory distress of newborn(P22)
| Other respiratory conditions originating in the perinatal period(P23–P28)
78# | Congenital pneumonia(P23)
79# | Neonatal aspiration syndromes(P24)
80# | Interstitial emphysema and related conditions originating in the perinatal period(P25)
81# | Pulmonary hemorrhage originating in the perinatal period(P26)
82# | Chronic respiratory disease originating in the perinatal period(P27)
83# | Atelectasis(P28.0–P28.1)
84 | All other respiratory conditions originating in the perinatal period(P28.2–P28.9)
| Infections specific to the perinatal period(P35–P39)
85# | Bacterial sepsis of newborn(P36)
86# | Omphalitis of newborn with or without mild hemorrhage(P38)
87 | All other infections specific to the perinatal period(P35,P37,P39)
| Hemorrhagic and hematological disorders of newborn(P50–P61)
88# | Neonatal hemorrhage(P50–P52,P54)
89# | Hemorrhagic disease of newborn(P53)
90# | Hemolytic disease of newborn due to isoimmunization and other perinatal jaundice(P55–P59)
91# | Hematological disorders(P60–P61)
92# | Syndrome of infant of a diabetic mother and neonatal diabetes mellitus(P70.0–P70.2)
93# | Necrotizing enterocolitis of newborn(P77)
94# | Hydrops fetalis not due to hemolytic disease(P83.2)
95 | Other perinatal conditions(P29,P70.3–P70.9,P71–P76,P78–P81,P83.0–P83.1,P83.3–P83.9,P90–P96)
# | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99)
96 | Anencephaly and similar malformations(Q00)
97 | Congenital hydrocephalus(Q03)
98 | Spina bifida(Q05)
99 | Other congenital malformations of nervous system(Q01–Q02,Q04,Q06–Q07)
100 | Congenital malformations of heart(Q20–Q24)
101 | Other congenital malformations of circulatory system(Q25–Q28)
102 | Congenital malformations of respiratory system(Q30–Q34)
103 | Congenital malformations of digestive system(Q35–Q45)
104 | Congenital malformations of genitourinary system(Q50–Q64)
105 | Congenital malformations and deformations of musculoskeletal system, limbs and integument(Q65–Q85)
106 | Down syndrome(Q90)
107 | Edward syndrome(Q91.0–Q91.3)
108 | Patau syndrome(Q91.4–Q91.7)
109 | Other congenital malformations and deformations(Q10–Q18,Q86–Q89)
110 | Other chromosomal abnormalities, not elsewhere classified(Q92–Q99)
| Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified(R00–R99)
111# | Sudden infant death syndrome(R95)
112 | Other symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified(R00–R53,R55–R94,R96–R99)
113 | All other diseases (residual)(F01–F99,H00–H57,L00–M99)
| External causes of mortality(*U01,V01–Y84)
# | Accidents (unintentional injuries)(V01–X59)
| Transport accidents(V01–V99)
114 | Motor vehicle accidents(V02–V04,V09.0,V09.2,V12–V14,V19.0–V19.2,V19.4–V19.6,V20–V79,V80.3–V80.5,V81.0–V81.1,V82.0–V82.1,V83–V86,V87.0–V87.8,V88.0–V88.8,V89.0,V89.2)
115 | Other and unspecified transport accidents(V01,V05–V06,V09.1,V09.3–V09.9,V10–V11,V15–V18,V19.3,V19.8–V19.9,V80.0–V80.2,V80.6–V80.9,V81.2–V81.9,V82.2–82.9,V87.9,V88.9,V89.1,V89.3,V89.9,V90–V99)
116 | Falls(W00–W19)
117 | Accidental discharge of firearms(W32–W34)
118 | Accidental drowning and submersion(W65–W74)
119 | Accidental suffocation and strangulation in bed(W75)
120 | Other accidental suffocation and strangulation(W76–W77,W81–W84)
121 | Accidental inhalation and ingestion of food or other objects causing obstruction of respiratory tract(W78–W80)
122 | Accidents caused by exposure to smoke, fire and flames(X00–X09)
123 | Accidental poisoning and exposure to noxious substances(X40–X49)
124 | Other and unspecified accidents(W20–W31,W35–W64,W85–W99,X10–X39,X50–X59)
# | Assault (homicide)(*U01,X85–Y09)
125 | Assault (homicide) by hanging, strangulation and suffocation(X91)
126 | Assault (homicide) by discharge of firearms(*U01.4,X93–X95)
127 | Neglect, abandonment and other maltreatment syndromes(Y06–Y07)
128 | Assault (homicide) by other and unspecified means(*U01.0–*U01.3,*U01.5–*U01.9,X85–X90,X92,X96–Y05,Y08–Y09)
129# | Complications of medical and surgical care(Y40–Y84)
130 | Other external causes(Y10–Y36)

†Causes labeled # are ranked to determine leading causes of infant death for specified population groups. Only mutually exclusive categories are numbered.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 2 Infant, neonatal, and postneonatal deaths, percentage of total deaths, and mortality rate for the 10 leading causes of infant death, by race and Hispanic origin and sex: United States, 2024

[Rates are infant (younger than 1 year), neonatal (younger than 28 days), and postneonatal (28 days through 11 months) deaths per 100,000 live births in specified group. Race and Hispanic-origin categories are consistent with 1997 Office of Management and Budget standards. Race and Hispanic origin are reported separately on the death certificate. People of Hispanic origin may be of any race. Data for Hispanic people are not tabulated separately by race; data for non-Hispanic people are tabulated by race. Data for racial and ethnic groups other than Black non-Hispanic and White non-Hispanic should be interpreted with caution because of inconsistencies between reporting Hispanic origin and race on birth and death certificates. Deaths are based on race and Hispanic origin of decedent; live births are based on race and Hispanic origin of mother. National linked files should be used to measure infant mortality for specific subgroups. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10)]

Rank^†^ | Cause of death (based on ICD–10), race and Hispanic origin, sex, and age group | Number^§,¶^ | Percent of total deaths^**^ | Death rate^§,¶^
| Infants, all races, all origins, both sexes
… | All causes | 20,050 | 100.0 | 552.5
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 4,061 | 20.3 | 111.9
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 2,941 | 14.7 | 81.0
3 | Sudden infant death syndrome(R95) | 1,351 | 6.7 | 37.2
4 | Accidents (unintentional injuries)(V01–X59) | 1,245 | 6.2 | 34.3
5 | Newborn affected by maternal complications of pregnancy(P01) | 1,193 | 6.0 | 32.9
6 | Bacterial sepsis of newborn(P36) | 603 | 3.0 | 16.6
7 | Newborn affected by complications of placenta, cord and membranes(P02) | 594 | 3.0 | 16.4
8 | Respiratory distress of newborn(P22) | 453 | 2.3 | 12.5
9 | Diseases of the circulatory system(I00–I99) | 376 | 1.9 | 10.4
10 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 368 | 1.8 | 10.1
… | All other causes(residual) | 6,865 | 34.2 | 189.2
| Infants, all races, all origins, male
… | All causes | 10,901 | 100.0 | 588.0
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 2,015 | 18.5 | 108.7
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 1,609 | 14.8 | 86.8
3 | Sudden infant death syndrome(R95) | 804 | 7.4 | 43.4
4 | Accidents (unintentional injuries)(V01–X59) | 669 | 6.1 | 36.1
5 | Newborn affected by maternal complications of pregnancy(P01) | 642 | 5.9 | 34.6
6 | Bacterial sepsis of newborn(P36) | 347 | 3.2 | 18.7
7 | Newborn affected by complications of placenta, cord and membranes(P02) | 310 | 2.8 | 16.7
8 | Respiratory distress of newborn(P22) | 271 | 2.5 | 14.6
9 | Neonatal hemorrhage(P50–P52,P54) | 214 | 2.0 | 11.5
10 | Diseases of the circulatory system(I00–I99) | 205 | 1.9 | 11.1
… | All other causes(residual) | 3,815 | 35.0 | 205.8
| Infants, all races, all origins, female
… | All causes | 9,149 | 100.0 | 515.4
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 2,046 | 22.4 | 115.3
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 1,332 | 14.6 | 75.0
3 | Accidents (unintentional injuries)(V01–X59) | 576 | 6.3 | 32.5
4 | Newborn affected by maternal complications of pregnancy(P01) | 551 | 6.0 | 31.0
5 | Sudden infant death syndrome(R95) | 547 | 6.0 | 30.8
6 | Newborn affected by complications of placenta, cord and membranes(P02) | 284 | 3.1 | 16.0
7 | Bacterial sepsis of newborn(P36) | 256 | 2.8 | 14.4
8 | Respiratory distress of newborn(P22) | 182 | 2.0 | 10.3
9 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 180 | 2.0 | 10.1
10 | Diseases of the circulatory system(I00–I99) | 171 | 1.9 | 9.6
… | All other causes(residual) | 3,024 | 33.1 | 170.4
| Infants, all races, Hispanic, both sexes
… | All causes | 5,038 | 100.0 | 511.9
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 1,247 | 24.8 | 126.7
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 742 | 14.7 | 75.4
3 | Newborn affected by maternal complications of pregnancy(P01) | 344 | 6.8 | 35.0
4 | Sudden infant death syndrome(R95) | 251 | 5.0 | 25.5
5 | Accidents (unintentional injuries)(V01–X59) | 206 | 4.1 | 20.9
6 | Bacterial sepsis of newborn(P36) | 157 | 3.1 | 16.0
7 | Newborn affected by complications of placenta, cord and membranes(P02) | 147 | 2.9 | 14.9
8 | Respiratory distress of newborn(P22) | 101 | 2.0 | 10.3
9 | Neonatal hemorrhage(P50–P52,P54) | 98 | 1.9 | 10.0
10 | Necrotizing enterocolitis of newborn(P77) | 94 | 1.9 | 9.6
… | All other causes(residual) | 1,651 | 32.8 | 167.8
| Infants, all races, Hispanic, male
… | All causes | 2,699 | 100.0 | 538.7
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 592 | 21.9 | 118.2
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 411 | 15.2 | 82.0
3 | Newborn affected by maternal complications of pregnancy(P01) | 179 | 6.6 | 35.7
4 | Sudden infant death syndrome(R95) | 166 | 6.2 | 33.1
5 | Accidents (unintentional injuries)(V01–X59) | 96 | 3.6 | 19.2
6 | Bacterial sepsis of newborn(P36) | 87 | 3.2 | 17.4
7 | Newborn affected by complications of placenta, cord and membranes(P02) | 73 | 2.7 | 14.6
8 | Neonatal hemorrhage(P50–P52,P54) | 72 | 2.7 | 14.4
9 | Respiratory distress of newborn(P22) | 58 | 2.1 | 11.6
10 | Necrotizing enterocolitis of newborn(P77) | 52 | 1.9 | 10.4
… | All other causes(residual) | 913 | 33.8 | 182.2
| Infants, all races, Hispanic, female
… | All causes | 2,339 | 100.0 | 484.2
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 655 | 28.0 | 135.6
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 331 | 14.2 | 68.5
3 | Newborn affected by maternal complications of pregnancy(P01) | 165 | 7.1 | 34.2
4 | Accidents (unintentional injuries)(V01–X59) | 110 | 4.7 | 22.8
5 | Sudden infant death syndrome(R95) | 85 | 3.6 | 17.6
6 | Newborn affected by complications of placenta, cord and membranes(P02) | 74 | 3.2 | 15.3
7 | Bacterial sepsis of newborn(P36) | 70 | 3.0 | 14.5
8 | Respiratory distress of newborn(P22) | 43 | 1.8 | 8.9
9 | Necrotizing enterocolitis of newborn(P77) | 42 | 1.8 | 8.7
10 | Diseases of the circulatory system(I00–I99) | 41 | 1.8 | 8.5
… | All other causes(residual) | 723 | 30.9 | 149.7
| Infants, American Indian and Alaska Native, non-Hispanic, both sexes
… | All causes | 209 | 100.0 | 870.1
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 35 | 16.7 | 145.7
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 25 | 12.0 | 104.1
3 | Accidents (unintentional injuries)(V01–X59) | 23 | 11.0 | 95.7
4 | Sudden infant death syndrome(R95) | 22 | 10.5 | 91.6
5 | Newborn affected by maternal complications of pregnancy(P01) | 13 | 6.2 | 54.1
6 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
7 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
7 | Assault (homicide)(*U01,X85–Y09) | §§ | §§ | §§
9 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
10 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
… | All other causes(residual) | 61 | 29.2 | 253.9
| Infants, American Indian and Alaska Native, non-Hispanic, male
… | All causes | 129 | 100.0 | 1,040.4
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 20 | 15.5 | 161.3
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 17 | 13.2 | 137.1
3 | Sudden infant death syndrome(R95) | 16 | 12.4 | 129.0
4 | Accidents (unintentional injuries)(V01–X59) | 14 | 10.9 | 112.9
5 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
6 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
7 | Assault (homicide)(*U01,X85–Y09) | §§ | §§ | §§
7 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
9 | Hydrops fetalis not due to hemolytic disease(P83.2) | §§ | §§ | §§
9 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
9 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
9 | Respiratory distress of newborn(P22) | §§ | §§ | §§
… | All other causes(residual) | 31 | 24.0 | 250.0
| Infants, American Indian and Alaska Native, non-Hispanic, female
… | All causes | 80 | 100.0 | 688.3
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 15 | 18.8 | 129.1
2 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
3 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
4 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
5 | Sudden infant death syndrome(R95) | §§ | §§ | §§
6 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
7 | Assault (homicide)(*U01,X85–Y09) | §§ | §§ | §§
7 | Newborn affected by other complications of labor and delivery(P03) | §§ | §§ | §§
7 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
7 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
… | All other causes(residual) | 23 | 28.8 | 197.9
| Infants, Asian, non-Hispanic, both sexes
… | All causes | 684 | 100.0 | 301.5
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 123 | 18.0 | 54.2
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 113 | 16.5 | 49.8
3 | Newborn affected by maternal complications of pregnancy(P01) | 51 | 7.5 | 22.5
4 | Bacterial sepsis of newborn(P36) | 31 | 4.5 | 13.7
5 | Newborn affected by complications of placenta, cord and membranes(P02) | 23 | 3.4 | 10.1
6 | Sudden infant death syndrome(R95) | 21 | 3.1 | 9.3
7 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 20 | 2.9 | 8.8
8 | Respiratory distress of newborn(P22) | 19 | 2.8 | 8.4
9 | Diseases of the circulatory system(I00–I99) | 18 | 2.6 | 7.9
10 | Neonatal hemorrhage(P50–P52,P54) | 16 | 2.3 | 7.1
… | All other causes(residual) | 249 | 36.4 | 109.8
| Infants, Asian, non-Hispanic, male
… | All causes | 357 | 100.0 | 305.9
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 61 | 17.1 | 52.3
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 61 | 17.1 | 52.3
3 | Newborn affected by maternal complications of pregnancy(P01) | 28 | 7.8 | 24.0
4 | Bacterial sepsis of newborn(P36) | 18 | 5.0 | 15.4
5 | Respiratory distress of newborn(P22) | 13 | 3.6 | 11.1
6 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 12 | 3.4 | 10.3
7 | Sudden infant death syndrome(R95) | 11 | 3.1 | 9.4
8 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
8 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
10 | Neonatal hemorrhage(P50–P52,P54) | §§ | §§ | §§
… | All other causes(residual) | 127 | 35.6 | 108.8
| Infants, Asian, non-Hispanic, female
… | All causes | 327 | 100.0 | 296.9
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 62 | 19.0 | 56.3
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 52 | 15.9 | 47.2
3 | Newborn affected by maternal complications of pregnancy(P01) | 23 | 7.0 | 20.9
4 | Diseases of the circulatory system(I00–I99) | 15 | 4.6 | 13.6
5 | Newborn affected by complications of placenta, cord and membranes(P02) | 14 | 4.3 | 12.7
6 | Bacterial sepsis of newborn(P36) | 13 | 4.0 | 11.8
7 | Sudden infant death syndrome(R95) | 10 | 3.1 | 9.1
8 | Neonatal hemorrhage(P50–P52,P54) | §§ | §§ | §§
8 | Intrauterine hypoxia and birth asphyxia(P20–P21) | §§ | §§ | §§
10 | Respiratory distress of newborn(P22) | §§ | §§ | §§
10 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
… | All other causes(residual) | 110 | 33.6 | 99.9
| Infants, Black, non-Hispanic, both sexes
… | All causes | 5,370 | 100.0 | 1,134.4
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 950 | 17.7 | 200.7
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 726 | 13.5 | 153.4
3 | Sudden infant death syndrome(R95) | 433 | 8.1 | 91.5
4 | Accidents (unintentional injuries)(V01–X59) | 432 | 8.0 | 91.3
5 | Newborn affected by maternal complications of pregnancy(P01) | 325 | 6.1 | 68.7
6 | Bacterial sepsis of newborn(P36) | 170 | 3.2 | 35.9
7 | Newborn affected by complications of placenta, cord and membranes(P02) | 147 | 2.7 | 31.1
8 | Respiratory distress of newborn(P22) | 139 | 2.6 | 29.4
9 | Diseases of the circulatory system(I00–I99) | 108 | 2.0 | 22.8
10 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 93 | 1.7 | 19.6
10 | Necrotizing enterocolitis of newborn(P77) | 93 | 1.7 | 19.6
… | All other causes(residual) | 1,754 | 32.7 | 370.5
| Infants, Black, non-Hispanic, male
… | All causes | 2,949 | 100.0 | 1,226.0
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 512 | 17.4 | 212.9
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 367 | 12.4 | 152.6
3 | Sudden infant death syndrome(R95) | 250 | 8.5 | 103.9
4 | Accidents (unintentional injuries)(V01–X59) | 234 | 7.9 | 97.3
5 | Newborn affected by maternal complications of pregnancy(P01) | 176 | 6.0 | 73.2
6 | Bacterial sepsis of newborn(P36) | 97 | 3.3 | 40.3
7 | Newborn affected by complications of placenta, cord and membranes(P02) | 86 | 2.9 | 35.8
8 | Respiratory distress of newborn(P22) | 83 | 2.8 | 34.5
9 | Diseases of the circulatory system(I00–I99) | 61 | 2.1 | 25.4
10 | Necrotizing enterocolitis of newborn(P77) | 55 | 1.9 | 22.9
… | All other causes(residual) | 1,028 | 34.9 | 427.4
| Infants, Black, non-Hispanic, female
… | All causes | 2,421 | 100.0 | 1,039.8
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 438 | 18.1 | 188.1
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 359 | 14.8 | 154.2
3 | Accidents (unintentional injuries)(V01–X59) | 198 | 8.2 | 85.0
4 | Sudden infant death syndrome(R95) | 183 | 7.6 | 78.6
5 | Newborn affected by maternal complications of pregnancy(P01) | 149 | 6.2 | 64.0
6 | Bacterial sepsis of newborn(P36) | 73 | 3.0 | 31.4
7 | Newborn affected by complications of placenta, cord and membranes(P02) | 61 | 2.5 | 26.2
8 | Respiratory distress of newborn(P22) | 56 | 2.3 | 24.1
9 | Diseases of the circulatory system(I00–I99) | 47 | 1.9 | 20.2
10 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 39 | 1.6 | 16.7
10 | Atelectasis(P28.0–P28.1) | 39 | 1.6 | 16.7
… | All other causes(residual) | 779 | 32.2 | 334.6
| Infants, Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes
… | All causes | 73 | 100.0 | 703.6
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 19 | 26.0 | 183.1
2 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
3 | Sudden infant death syndrome(R95) | §§ | §§ | §§
3 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
5 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
6 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
7 | Respiratory distress of newborn(P22) | §§ | §§ | §§
7 | Newborn affected by other complications of labor and delivery(P03) | §§ | §§ | §§
7 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
7 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
7 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
7 | Assault (homicide)(*U01,X85–Y09) | §§ | §§ | §§
7 | Diarrhea and gastroenteritis of infectious origin(A09) | §§ | §§ | §§
7 | Pulmonary hemorrhage originating in the perinatal period(P26) | §§ | §§ | §§
7 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
… | All other causes(residual) | 18 | 24.7 | 173.5
| Infants, Native Hawaiian and Other Pacific Islander, non-Hispanic, male
… | All causes | 43 | 100.0 | 810.4
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 12 | 27.9 | 226.2
2 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
2 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
2 | Sudden infant death syndrome(R95) | §§ | §§ | §§
5 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
6 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
7 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
7 | Diarrhea and gastroenteritis of infectious origin(A09) | §§ | §§ | §§
7 | Respiratory distress of newborn(P22) | §§ | §§ | §§
7 | Newborn affected by other complications of labor and delivery(P03) | §§ | §§ | §§
7 | Assault (homicide)(*U01,X85–Y09) | §§ | §§ | §§
7 | Pulmonary hemorrhage originating in the perinatal period(P26) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Infants, Native Hawaiian and Other Pacific Islander, non-Hispanic, female
… | All causes | 30 | 100.0 | 591.8
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
2 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
4 | Sudden infant death syndrome(R95) | §§ | §§ | §§
5 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
5 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
5 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
5 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
5 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
… | All other causes(residual) | 10 | 33.3 | 197.3
| Infants, White, non-Hispanic, both sexes
… | All causes | 7,662 | 100.0 | 429.7
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 1,751 | 22.9 | 98.2
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 938 | 12.2 | 52.6
3 | Sudden infant death syndrome(R95) | 529 | 6.9 | 29.7
4 | Accidents (unintentional injuries)(V01–X59) | 492 | 6.4 | 27.6
5 | Newborn affected by maternal complications of pregnancy(P01) | 386 | 5.0 | 21.6
6 | Newborn affected by complications of placenta, cord and membranes(P02) | 243 | 3.2 | 13.6
7 | Bacterial sepsis of newborn(P36) | 216 | 2.8 | 12.1
8 | Respiratory distress of newborn(P22) | 161 | 2.1 | 9.0
9 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 155 | 2.0 | 8.7
10 | Neonatal hemorrhage(P50–P52,P54) | 151 | 2.0 | 8.5
… | All other causes(residual) | 2,640 | 34.5 | 148.1
| Infants, White, non-Hispanic, male
… | All causes | 4,162 | 100.0 | 455.8
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 889 | 21.4 | 97.4
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 514 | 12.3 | 56.3
3 | Sudden infant death syndrome(R95) | 306 | 7.4 | 33.5
4 | Accidents (unintentional injuries)(V01–X59) | 274 | 6.6 | 30.0
5 | Newborn affected by maternal complications of pregnancy(P01) | 212 | 5.1 | 23.2
6 | Bacterial sepsis of newborn(P36) | 125 | 3.0 | 13.7
7 | Newborn affected by complications of placenta, cord and membranes(P02) | 122 | 2.9 | 13.4
8 | Respiratory distress of newborn(P22) | 97 | 2.3 | 10.6
9 | Neonatal hemorrhage(P50–P52,P54) | 92 | 2.2 | 10.1
10 | Diseases of the circulatory system(I00–I99) | 85 | 2.0 | 9.3
… | All other causes(residual) | 1,446 | 34.7 | 158.4
| Infants, White, non-Hispanic, female
… | All causes | 3,500 | 100.0 | 402.3
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 862 | 24.6 | 99.1
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 424 | 12.1 | 48.7
3 | Sudden infant death syndrome(R95) | 223 | 6.4 | 25.6
4 | Accidents (unintentional injuries)(V01–X59) | 218 | 6.2 | 25.1
5 | Newborn affected by maternal complications of pregnancy(P01) | 174 | 5.0 | 20.0
6 | Newborn affected by complications of placenta, cord and membranes(P02) | 121 | 3.5 | 13.9
7 | Bacterial sepsis of newborn(P36) | 91 | 2.6 | 10.5
8 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 83 | 2.4 | 9.5
9 | Respiratory distress of newborn(P22) | 64 | 1.8 | 7.4
10 | Diseases of the circulatory system(I00–I99) | 61 | 1.7 | 7.0
… | All other causes(residual) | 1,179 | 33.7 | 135.5
| Neonates, all races, all origins, both sexes
… | All causes | 13,246 | 100.0 | 365.0
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 2,876 | 21.7 | 79.3
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 2,867 | 21.6 | 79.0
3 | Newborn affected by maternal complications of pregnancy(P01) | 1,177 | 8.9 | 32.4
4 | Newborn affected by complications of placenta, cord and membranes(P02) | 586 | 4.4 | 16.1
5 | Bacterial sepsis of newborn(P36) | 578 | 4.4 | 15.9
6 | Respiratory distress of newborn(P22) | 441 | 3.3 | 12.2
7 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 358 | 2.7 | 9.9
8 | Neonatal hemorrhage(P50–P52,P54) | 332 | 2.5 | 9.1
9 | Necrotizing enterocolitis of newborn(P77) | 286 | 2.2 | 7.9
10 | Atelectasis(P28.0–P28.1) | 273 | 2.1 | 7.5
… | All other causes(residual) | 3,472 | 26.2 | 95.7
| Neonates, all races, all origins, male
… | All causes | 7,125 | 100.0 | 384.3
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 1,565 | 22.0 | 84.4
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 1,443 | 20.3 | 77.8
3 | Newborn affected by maternal complications of pregnancy(P01) | 632 | 8.9 | 34.1
4 | Bacterial sepsis of newborn(P36) | 336 | 4.7 | 18.1
5 | Newborn affected by complications of placenta, cord and membranes(P02) | 306 | 4.3 | 16.5
6 | Respiratory distress of newborn(P22) | 265 | 3.7 | 14.3
7 | Neonatal hemorrhage(P50–P52,P54) | 206 | 2.9 | 11.1
8 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 182 | 2.6 | 9.8
9 | Necrotizing enterocolitis of newborn(P77) | 160 | 2.2 | 8.6
10 | Atelectasis(P28.0–P28.1) | 148 | 2.1 | 8.0
… | All other causes(residual) | 1,882 | 26.4 | 101.5
| Neonates, all races, all origins, female
… | All causes | 6,121 | 100.0 | 344.9
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 1,433 | 23.4 | 80.7
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 1,302 | 21.3 | 73.4
3 | Newborn affected by maternal complications of pregnancy(P01) | 545 | 8.9 | 30.7
4 | Newborn affected by complications of placenta, cord and membranes(P02) | 280 | 4.6 | 15.8
5 | Bacterial sepsis of newborn(P36) | 242 | 4.0 | 13.6
6 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 176 | 2.9 | 9.9
6 | Respiratory distress of newborn(P22) | 176 | 2.9 | 9.9
8 | Necrotizing enterocolitis of newborn(P77) | 126 | 2.1 | 7.1
8 | Neonatal hemorrhage(P50–P52,P54) | 126 | 2.1 | 7.1
10 | Atelectasis(P28.0–P28.1) | 125 | 2.0 | 7.0
… | All other causes(residual) | 1,590 | 26.0 | 89.6
| Neonates, all races, Hispanic, both sexes
… | All causes | 3,505 | 100.0 | 356.2
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 894 | 25.5 | 90.8
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 728 | 20.8 | 74.0
3 | Newborn affected by maternal complications of pregnancy(P01) | 340 | 9.7 | 34.5
4 | Bacterial sepsis of newborn(P36) | 149 | 4.3 | 15.1
5 | Newborn affected by complications of placenta, cord and membranes(P02) | 146 | 4.2 | 14.8
6 | Respiratory distress of newborn(P22) | 98 | 2.8 | 10.0
7 | Neonatal hemorrhage(P50–P52,P54) | 94 | 2.7 | 9.6
8 | Necrotizing enterocolitis of newborn(P77) | 84 | 2.4 | 8.5
9 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 77 | 2.2 | 7.8
10 | Atelectasis(P28.0–P28.1) | 65 | 1.9 | 6.6
… | All other causes(residual) | 830 | 23.7 | 84.3
| Neonates, all races, Hispanic, male
… | All causes | 1,861 | 100.0 | 371.4
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 430 | 23.1 | 85.8
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 404 | 21.7 | 80.6
3 | Newborn affected by maternal complications of pregnancy(P01) | 176 | 9.5 | 35.1
4 | Bacterial sepsis of newborn(P36) | 84 | 4.5 | 16.8
5 | Newborn affected by complications of placenta, cord and membranes(P02) | 73 | 3.9 | 14.6
6 | Neonatal hemorrhage(P50–P52,P54) | 70 | 3.8 | 14.0
7 | Respiratory distress of newborn(P22) | 57 | 3.1 | 11.4
8 | Necrotizing enterocolitis of newborn(P77) | 45 | 2.4 | 9.0
9 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 38 | 2.0 | 7.6
10 | Atelectasis(P28.0–P28.1) | 36 | 1.9 | 7.2
… | All other causes(residual) | 448 | 24.1 | 89.4
| Neonates, all races, Hispanic, female
… | All causes | 1,644 | 100.0 | 340.3
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 464 | 28.2 | 96.1
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 324 | 19.7 | 67.1
3 | Newborn affected by maternal complications of pregnancy(P01) | 164 | 10.0 | 33.9
4 | Newborn affected by complications of placenta, cord and membranes(P02) | 73 | 4.4 | 15.1
5 | Bacterial sepsis of newborn(P36) | 65 | 4.0 | 13.5
6 | Respiratory distress of newborn(P22) | 41 | 2.5 | 8.5
7 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 39 | 2.4 | 8.1
7 | Necrotizing enterocolitis of newborn(P77) | 39 | 2.4 | 8.1
9 | Atelectasis(P28.0–P28.1) | 29 | 1.8 | 6.0
10 | Neonatal hemorrhage(P50–P52,P54) | 24 | 1.5 | 5.0
… | All other causes(residual) | 382 | 23.2 | 79.1
| Neonates, American Indian and Alaska Native, non-Hispanic, both sexes
… | All causes | 115 | 100.0 | 478.7
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 24 | 20.9 | 99.9
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 23 | 20.0 | 95.7
3 | Newborn affected by maternal complications of pregnancy(P01) | 13 | 11.3 | 54.1
4 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
5 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
6 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
7 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
8 | Newborn affected by other complications of labor and delivery(P03) | §§ | §§ | §§
8 | Intrauterine hypoxia and birth asphyxia(P20–P21) | §§ | §§ | §§
8 | Hydrops fetalis not due to hemolytic disease(P83.2) | §§ | §§ | §§
… | All other causes(residual) | 21 | 18.3 | 87.4
| Neonates, American Indian and Alaska Native, non-Hispanic, male
… | All causes | 68 | 100.0 | 548.4
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 17 | 25.0 | 137.1
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 12 | 17.6 | 96.8
3 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
4 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
5 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
5 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
7 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
7 | Hydrops fetalis not due to hemolytic disease(P83.2) | §§ | §§ | §§
9 | Intrauterine hypoxia and birth asphyxia(P20–P21) | §§ | §§ | §§
9 | Respiratory distress of newborn(P22) | §§ | §§ | §§
9 | Neonatal hemorrhage(P50–P52,P54) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Neonates, American Indian and Alaska Native, non-Hispanic, female
… | All causes | 47 | 100.0 | 404.4
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 11 | 23.4 | 94.6
2 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
4 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
4 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
6 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
6 | Newborn affected by other complications of labor and delivery(P03) | §§ | §§ | §§
8 | Intrauterine hypoxia and birth asphyxia(P20–P21) | §§ | §§ | §§
8 | Atelectasis(P28.0–P28.1) | §§ | §§ | §§
8 | Sudden infant death syndrome(R95) | §§ | §§ | §§
8 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
8 | Neonatal aspiration syndromes(P24) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Neonates, Asian, non-Hispanic, both sexes
… | All causes | 519 | 100.0 | 228.8
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 107 | 20.6 | 47.2
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 88 | 17.0 | 38.8
3 | Newborn affected by maternal complications of pregnancy(P01) | 51 | 9.8 | 22.5
4 | Bacterial sepsis of newborn(P36) | 30 | 5.8 | 13.2
5 | Newborn affected by complications of placenta, cord and membranes(P02) | 22 | 4.2 | 9.7
6 | Respiratory distress of newborn(P22) | 19 | 3.7 | 8.4
6 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 19 | 3.7 | 8.4
8 | Neonatal hemorrhage(P50–P52,P54) | 16 | 3.1 | 7.1
9 | Necrotizing enterocolitis of newborn(P77) | 10 | 1.9 | 4.4
10 | Hydrops fetalis not due to hemolytic disease(P83.2) | 9 | 1.7 | *
… | All other causes(residual) | 148 | 28.5 | 65.2
| Neonates, Asian, non-Hispanic, male
… | All causes | 283 | 100.0 | 242.5
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 59 | 20.8 | 50.6
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 47 | 16.6 | 40.3
3 | Newborn affected by maternal complications of pregnancy(P01) | 28 | 9.9 | 24.0
4 | Bacterial sepsis of newborn(P36) | 18 | 6.4 | 15.4
5 | Respiratory distress of newborn(P22) | 13 | 4.6 | 11.1
6 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 11 | 3.9 | 9.4
7 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
8 | Neonatal hemorrhage(P50–P52,P54) | §§ | §§ | §§
9 | Hematological disorders(P60–P61) | §§ | §§ | §§
10 | Newborn affected by other complications of labor and delivery(P03) | §§ | §§ | §§
… | All other causes(residual) | 79 | 27.9 | 67.7
| Neonates, Asian, non-Hispanic, female
… | All causes | 236 | 100.0 | 214.3
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 48 | 20.3 | 43.6
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 41 | 17.4 | 37.2
3 | Newborn affected by maternal complications of pregnancy(P01) | 23 | 9.7 | 20.9
4 | Newborn affected by complications of placenta, cord and membranes(P02) | 13 | 5.5 | 11.8
5 | Bacterial sepsis of newborn(P36) | 12 | 5.1 | 10.9
6 | Neonatal hemorrhage(P50–P52,P54) | §§ | §§ | §§
6 | Intrauterine hypoxia and birth asphyxia(P20–P21) | §§ | §§ | §§
8 | Respiratory distress of newborn(P22) | §§ | §§ | §§
8 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
10 | Hydrops fetalis not due to hemolytic disease(P83.2) | §§ | §§ | §§
… | All other causes(residual) | 66 | 28.0 | 59.9
| Neonates, Black, non-Hispanic, both sexes
… | All causes | 3,259 | 100.0 | 688.5
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 925 | 28.4 | 195.4
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 463 | 14.2 | 97.8
3 | Newborn affected by maternal complications of pregnancy(P01) | 318 | 9.8 | 67.2
4 | Bacterial sepsis of newborn(P36) | 163 | 5.0 | 34.4
5 | Newborn affected by complications of placenta, cord and membranes(P02) | 145 | 4.4 | 30.6
6 | Respiratory distress of newborn(P22) | 136 | 4.2 | 28.7
7 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 89 | 2.7 | 18.8
8 | Necrotizing enterocolitis of newborn(P77) | 80 | 2.5 | 16.9
9 | Atelectasis(P28.0–P28.1) | 75 | 2.3 | 15.8
10 | Neonatal hemorrhage(P50–P52,P54) | 62 | 1.9 | 13.1
… | All other causes(residual) | 803 | 24.6 | 169.6
| Neonates, Black, non-Hispanic, male
… | All causes | 1,776 | 100.0 | 738.3
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 493 | 27.8 | 205.0
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 237 | 13.3 | 98.5
3 | Newborn affected by maternal complications of pregnancy(P01) | 172 | 9.7 | 71.5
4 | Bacterial sepsis of newborn(P36) | 92 | 5.2 | 38.2
5 | Newborn affected by complications of placenta, cord and membranes(P02) | 84 | 4.7 | 34.9
6 | Respiratory distress of newborn(P22) | 81 | 4.6 | 33.7
7 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 52 | 2.9 | 21.6
8 | Necrotizing enterocolitis of newborn(P77) | 46 | 2.6 | 19.1
9 | Atelectasis(P28.0–P28.1) | 37 | 2.1 | 15.4
10 | Neonatal hemorrhage(P50–P52,P54) | 32 | 1.8 | 13.3
… | All other causes(residual) | 450 | 25.3 | 187.1
| Neonates, Black, non-Hispanic, female
… | All causes | 1,483 | 100.0 | 636.9
1 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 432 | 29.1 | 185.5
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 226 | 15.2 | 97.1
3 | Newborn affected by maternal complications of pregnancy(P01) | 146 | 9.8 | 62.7
4 | Bacterial sepsis of newborn(P36) | 71 | 4.8 | 30.5
5 | Newborn affected by complications of placenta, cord and membranes(P02) | 61 | 4.1 | 26.2
6 | Respiratory distress of newborn(P22) | 55 | 3.7 | 23.6
7 | Atelectasis(P28.0–P28.1) | 38 | 2.6 | 16.3
8 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 37 | 2.5 | 15.9
9 | Necrotizing enterocolitis of newborn(P77) | 34 | 2.3 | 14.6
10 | Neonatal hemorrhage(P50–P52,P54) | 30 | 2.0 | 12.9
… | All other causes(residual) | 353 | 23.8 | 151.6
| Neonates, Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes
… | All causes | 37 | 100.0 | 356.6
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 10 | 27.0 | 96.4
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
3 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
4 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
5 | Newborn affected by other complications of labor and delivery(P03) | §§ | §§ | §§
5 | Respiratory distress of newborn(P22) | §§ | §§ | §§
5 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
5 | Sudden infant death syndrome(R95) | §§ | §§ | §§
5 | Pulmonary hemorrhage originating in the perinatal period(P26) | §§ | §§ | §§
5 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Neonates, Native Hawaiian and Other Pacific Islander, non-Hispanic, male
… | All causes | 23 | 100.0 | 433.5
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
2 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
4 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
5 | Newborn affected by other complications of labor and delivery(P03) | §§ | §§ | §§
5 | Respiratory distress of newborn(P22) | §§ | §§ | §§
5 | Pulmonary hemorrhage originating in the perinatal period(P26) | §§ | §§ | §§
5 | Sudden infant death syndrome(R95) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Neonates, Native Hawaiian and Other Pacific Islander, non-Hispanic, female
… | All causes | 14 | 100.0 | 276.2
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
3 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
3 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
3 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
3 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Neonates, White, non-Hispanic, both sexes
… | All causes | 5,139 | 100.0 | 288.2
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 1,281 | 24.9 | 71.8
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 914 | 17.8 | 51.3
3 | Newborn affected by maternal complications of pregnancy(P01) | 382 | 7.4 | 21.4
4 | Newborn affected by complications of placenta, cord and membranes(P02) | 241 | 4.7 | 13.5
5 | Bacterial sepsis of newborn(P36) | 207 | 4.0 | 11.6
6 | Respiratory distress of newborn(P22) | 156 | 3.0 | 8.7
7 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 151 | 2.9 | 8.5
8 | Neonatal hemorrhage(P50–P52,P54) | 145 | 2.8 | 8.1
9 | Atelectasis(P28.0–P28.1) | 108 | 2.1 | 6.1
10 | Necrotizing enterocolitis of newborn(P77) | 89 | 1.7 | 5.0
… | All other causes(residual) | 1,465 | 28.5 | 82.2
| Neonates, White, non-Hispanic, male
… | All causes | 2,757 | 100.0 | 301.9
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 657 | 23.8 | 72.0
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 500 | 18.1 | 54.8
3 | Newborn affected by maternal complications of pregnancy(P01) | 210 | 7.6 | 23.0
4 | Bacterial sepsis of newborn(P36) | 122 | 4.4 | 13.4
5 | Newborn affected by complications of placenta, cord and membranes(P02) | 121 | 4.4 | 13.3
6 | Respiratory distress of newborn(P22) | 95 | 3.4 | 10.4
7 | Neonatal hemorrhage(P50–P52,P54) | 88 | 3.2 | 9.6
8 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 70 | 2.5 | 7.7
9 | Atelectasis(P28.0–P28.1) | 61 | 2.2 | 6.7
10 | Necrotizing enterocolitis of newborn(P77) | 51 | 1.8 | 5.6
… | All other causes(residual) | 782 | 28.4 | 85.6
| Neonates, White, non-Hispanic, female
… | All causes | 2,382 | 100.0 | 273.8
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 624 | 26.2 | 71.7
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 414 | 17.4 | 47.6
3 | Newborn affected by maternal complications of pregnancy(P01) | 172 | 7.2 | 19.8
4 | Newborn affected by complications of placenta, cord and membranes(P02) | 120 | 5.0 | 13.8
5 | Bacterial sepsis of newborn(P36) | 85 | 3.6 | 9.8
6 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 81 | 3.4 | 9.3
7 | Respiratory distress of newborn(P22) | 61 | 2.6 | 7.0
8 | Neonatal hemorrhage(P50–P52,P54) | 57 | 2.4 | 6.6
9 | Atelectasis(P28.0–P28.1) | 47 | 2.0 | 5.4
10 | Necrotizing enterocolitis of newborn(P77) | 38 | 1.6 | 4.4
… | All other causes(residual) | 683 | 28.7 | 78.5
| Postneonates, all races, all origins, both sexes
… | All causes | 6,804 | 100.0 | 187.5
1 | Sudden infant death syndrome(R95) | 1,215 | 17.9 | 33.5
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 1,185 | 17.4 | 32.7
3 | Accidents (unintentional injuries)(V01–X59) | 1,081 | 15.9 | 29.8
4 | Diseases of the circulatory system(I00–I99) | 293 | 4.3 | 8.1
5 | Assault (homicide)(*U01,X85–Y09) | 219 | 3.2 | 6.0
6 | Diarrhea and gastroenteritis of infectious origin(A09) | 141 | 2.1 | 3.9
7 | Septicemia(A40–A41) | 121 | 1.8 | 3.3
8 | Chronic respiratory disease originating in the perinatal period(P27) | 116 | 1.7 | 3.2
9 | Influenza and pneumonia(J09–J18) | 99 | 1.5 | 2.7
10 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 74 | 1.1 | 2.0
… | All other causes(residual) | 2,260 | 33.2 | 62.3
| Postneonates, all races, all origins, male
… | All causes | 3,776 | 100.0 | 203.7
1 | Sudden infant death syndrome(R95) | 729 | 19.3 | 39.3
2 | Accidents (unintentional injuries)(V01–X59) | 590 | 15.6 | 31.8
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 572 | 15.1 | 30.9
4 | Diseases of the circulatory system(I00–I99) | 159 | 4.2 | 8.6
5 | Assault (homicide)(*U01,X85–Y09) | 138 | 3.7 | 7.4
6 | Diarrhea and gastroenteritis of infectious origin(A09) | 81 | 2.1 | 4.4
7 | Chronic respiratory disease originating in the perinatal period(P27) | 68 | 1.8 | 3.7
8 | Septicemia(A40–A41) | 67 | 1.8 | 3.6
9 | Influenza and pneumonia(J09–J18) | 61 | 1.6 | 3.3
10 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 44 | 1.2 | 2.4
… | All other causes(residual) | 1,267 | 33.6 | 68.3
| Postneonates, all races, all origins, female
… | All causes | 3,028 | 100.0 | 170.6
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 613 | 20.2 | 34.5
2 | Accidents (unintentional injuries)(V01–X59) | 491 | 16.2 | 27.7
3 | Sudden infant death syndrome(R95) | 486 | 16.1 | 27.4
4 | Diseases of the circulatory system(I00–I99) | 134 | 4.4 | 7.5
5 | Assault (homicide)(*U01,X85–Y09) | 81 | 2.7 | 4.6
6 | Diarrhea and gastroenteritis of infectious origin(A09) | 60 | 2.0 | 3.4
7 | Septicemia(A40–A41) | 54 | 1.8 | 3.0
8 | Chronic respiratory disease originating in the perinatal period(P27) | 48 | 1.6 | 2.7
9 | Influenza and pneumonia(J09–J18) | 38 | 1.3 | 2.1
10 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 30 | 1.0 | 1.7
… | All other causes(residual) | 993 | 32.8 | 55.9
| Postneonates, all races, Hispanic, both sexes
… | All causes | 1,533 | 100.0 | 155.8
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 353 | 23.0 | 35.9
2 | Sudden infant death syndrome(R95) | 235 | 15.3 | 23.9
3 | Accidents (unintentional injuries)(V01–X59) | 181 | 11.8 | 18.4
4 | Diseases of the circulatory system(I00–I99) | 60 | 3.9 | 6.1
5 | Assault (homicide)(*U01,X85–Y09) | 58 | 3.8 | 5.9
6 | Diarrhea and gastroenteritis of infectious origin(A09) | 39 | 2.5 | 4.0
7 | Septicemia(A40–A41) | 28 | 1.8 | 2.8
8 | Chronic respiratory disease originating in the perinatal period(P27) | 24 | 1.6 | 2.4
9 | Influenza and pneumonia(J09–J18) | 18 | 1.2 | 1.8
10 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 14 | 0.9 | 1.4
… | All other causes(residual) | 523 | 34.1 | 53.1
| Postneonates, all races, Hispanic, male
… | All causes | 838 | 100.0 | 167.3
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 162 | 19.3 | 32.3
2 | Sudden infant death syndrome(R95) | 157 | 18.7 | 31.3
3 | Accidents (unintentional injuries)(V01–X59) | 87 | 10.4 | 17.4
4 | Assault (homicide)(*U01,X85–Y09) | 40 | 4.8 | 8.0
5 | Diseases of the circulatory system(I00–I99) | 31 | 3.7 | 6.2
6 | Septicemia(A40–A41) | 22 | 2.6 | 4.4
7 | Diarrhea and gastroenteritis of infectious origin(A09) | 18 | 2.1 | 3.6
8 | Chronic respiratory disease originating in the perinatal period(P27) | 13 | 1.6 | 2.6
9 | Diseases of the blood and blood–forming organs andcertain disorders invoving the immune mechanism(D50–D89) | §§ | §§ | §§
10 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
10 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
10 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
… | All other causes(residual) | 278 | 33.2 | 55.5
| Postneonates, all races, Hispanic, female
… | All causes | 695 | 100.0 | 143.9
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 191 | 27.5 | 39.5
2 | Accidents (unintentional injuries)(V01–X59) | 94 | 13.5 | 19.5
3 | Sudden infant death syndrome(R95) | 78 | 11.2 | 16.1
4 | Diseases of the circulatory system(I00–I99) | 29 | 4.2 | 6.0
5 | Diarrhea and gastroenteritis of infectious origin(A09) | 21 | 3.0 | 4.3
6 | Assault (homicide)(*U01,X85–Y09) | 18 | 2.6 | 3.7
7 | Influenza and pneumonia(J09–J18) | 11 | 1.6 | 2.3
7 | Chronic respiratory disease originating in the perinatal period(P27) | 11 | 1.6 | 2.3
9 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
10 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 229 | 32.9 | 47.4
| Postneonates, American Indian and Alaska Native, non-Hispanic, both sexes
… | All causes | 94 | 100.0 | 391.3
1 | Sudden infant death syndrome(R95) | 21 | 22.3 | 87.4
2 | Accidents (unintentional injuries)(V01–X59) | 16 | 17.0 | 66.6
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 12 | 12.8 | 50.0
4 | Assault (homicide)(*U01,X85–Y09) | §§ | §§ | §§
5 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
6 | Septicemia(A40–A41) | §§ | §§ | §§
6 | Diseases of the blood and blood–forming organs andcertain disorders invoving the immune mechanism(D50–D89) | §§ | §§ | §§
6 | Hernia of abdominal cavity and intestinal obstruction without hernia(K40–K46,K56) | §§ | §§ | §§
6 | Meningitis(G00,G03) | §§ | §§ | §§
6 | Acute upper respiratory infections(J00–J06) | §§ | §§ | §§
6 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
6 | Renal failure and other disorders of kidney(N17–N19,N25,N27) | §§ | §§ | §§
6 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
6 | Respiratory distress of newborn(P22) | §§ | §§ | §§
6 | Chronic respiratory disease originating in the perinatal period(P27) | §§ | §§ | §§
6 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
… | All other causes(residual) | 23 | 24.5 | 95.7
| Postneonates, American Indian and Alaska Native, non-Hispanic, male
… | All causes | 61 | 100.0 | 492.0
1 | Sudden infant death syndrome(R95) | 16 | 26.2 | 129.0
2 | Accidents (unintentional injuries)(V01–X59) | 10 | 16.4 | 80.7
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Assault (homicide)(*U01,X85–Y09) | §§ | §§ | §§
5 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
6 | Diseases of the blood and blood–forming organs andcertain disorders invoving the immune mechanism(D50–D89) | §§ | §§ | §§
6 | Septicemia(A40–A41) | §§ | §§ | §§
6 | Meningitis(G00,G03) | §§ | §§ | §§
6 | Acute upper respiratory infections(J00–J06) | §§ | §§ | §§
6 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
6 | Hernia of abdominal cavity and intestinal obstruction without hernia(K40–K46,K56) | §§ | §§ | §§
6 | Respiratory distress of newborn(P22) | §§ | §§ | §§
6 | Chronic respiratory disease originating in the perinatal period(P27) | §§ | §§ | §§
… | All other causes(residual) | 12 | 19.7 | 96.8
| Postneonates, American Indian and Alaska Native, non-Hispanic, female
… | All causes | 33 | 100.0 | 283.9
1 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
2 | Sudden infant death syndrome(R95) | §§ | §§ | §§
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
4 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
4 | Assault (homicide)(*U01,X85–Y09) | §§ | §§ | §§
6 | Renal failure and other disorders of kidney(N17–N19,N25,N27) | §§ | §§ | §§
6 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
6 | Necrotizing enterocolitis of newborn(P77) | §§ | §§ | §§
… | All other causes(residual) | 11 | 33.3 | 94.6
| Postneonates, Asian, non-Hispanic, both sexes
… | All causes | 165 | 100.0 | 72.7
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 35 | 21.2 | 15.4
2 | Sudden infant death syndrome(R95) | 20 | 12.1 | 8.8
3 | Diseases of the circulatory system(I00–I99) | 16 | 9.7 | 7.1
4 | Accidents (unintentional injuries)(V01–X59) | 14 | 8.5 | 6.2
5 | Diarrhea and gastroenteritis of infectious origin(A09) | §§ | §§ | §§
5 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
7 | Chronic respiratory disease originating in the perinatal period(P27) | §§ | §§ | §§
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
9 | Septicemia(A40–A41) | §§ | §§ | §§
10 | Hernia of abdominal cavity and intestinal obstruction without hernia(K40–K46,K56) | §§ | §§ | §§
10 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
10 | Volume depletion, disorders of fluid, electrolyte and acid–base balance(E86–E87) | §§ | §§ | §§
10 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
10 | Meningitis(G00,G03) | §§ | §§ | §§
10 | Infantile spinal muscular atrophy, type I (Werdnig-Hoffman)(G12.0) | §§ | §§ | §§
10 | Anoxic brain damage, not elsewhere classified(G93.1) | §§ | §§ | §§
10 | Renal failure and other disorders of kidney(N17–N19,N25,N27) | §§ | §§ | §§
10 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
10 | Intrauterine hypoxia and birth asphyxia(P20–P21) | §§ | §§ | §§
10 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
10 | Hemolytic disease of newborn due to isoimmunization and other perinatal jaundice(P55–P59) | §§ | §§ | §§
… | All other causes(residual) | 47 | 28.5 | 20.7
| Postneonates, Asian, non-Hispanic, male
… | All causes | 74 | 100.0 | 63.4
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 14 | 18.9 | 12.0
2 | Sudden infant death syndrome(R95) | 10 | 13.5 | 8.6
3 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
4 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
5 | Diarrhea and gastroenteritis of infectious origin(A09) | §§ | §§ | §§
5 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
5 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
5 | Chronic respiratory disease originating in the perinatal period(P27) | §§ | §§ | §§
9 | In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | §§ | §§ | §§
9 | Meningitis(G00,G03) | §§ | §§ | §§
9 | Infantile spinal muscular atrophy, type I (Werdnig–Hoffman)(G12.0) | §§ | §§ | §§
9 | Hernia of abdominal cavity and intestinal obstruction without hernia(K40–K46,K56) | §§ | §§ | §§
9 | Intrauterine hypoxia and birth asphyxia(P20–P21) | §§ | §§ | §§
9 | Septicemia(A40–A41) | §§ | §§ | §§
… | All other causes(residual) | 24 | 32.4 | 20.6
| Postneonates, Asian, non-Hispanic, female
… | All causes | 91 | 100.0 | 82.6
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 21 | 23.1 | 19.1
2 | Diseases of the circulatory system(I00–I99) | 13 | 14.3 | 11.8
3 | Sudden infant death syndrome(R95) | 10 | 11.0 | 9.1
4 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
5 | Diarrhea and gastroenteritis of infectious origin(A09) | §§ | §§ | §§
5 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | §§ | §§ | §§
7 | Chronic respiratory disease originating in the perinatal period(P27) | §§ | §§ | §§
8 | Septicemia(A40–A41) | §§ | §§ | §§
8 | Malignant neoplasms(C00–C97) | §§ | §§ | §§
8 | Volume depletion, disorders of fluid, electrolyte and acid–base balance(E86–E87) | §§ | §§ | §§
8 | Anoxic brain damage, not elsewhere classified(G93.1) | §§ | §§ | §§
8 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
8 | Renal failure and other disorders of kidney(N17–N19,N25,N27) | §§ | §§ | §§
8 | Newborn affected by complications of placenta, cord and membranes(P02) | §§ | §§ | §§
8 | Bacterial sepsis of newborn(P36) | §§ | §§ | §§
8 | Hemolytic disease of newborn due to isoimmunization and other perinatal jaundice(P55–P59) | §§ | §§ | §§
… | All other causes(residual) | 23 | 25.3 | 20.9
| Postneonates, Black, non-Hispanic, both sexes
… | All causes | 2,111 | 100.0 | 445.9
1 | Sudden infant death syndrome(R95) | 394 | 18.7 | 83.2
2 | Accidents (unintentional injuries)(V01–X59) | 380 | 18.0 | 80.3
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 263 | 12.5 | 55.6
4 | Diseases of the circulatory system(I00–I99) | 89 | 4.2 | 18.8
5 | Assault (homicide)(*U01,X85–Y09) | 78 | 3.7 | 16.5
6 | Diarrhea and gastroenteritis of infectious origin(A09) | 51 | 2.4 | 10.8
7 | Septicemia(A40–A41) | 45 | 2.1 | 9.5
8 | Chronic respiratory disease originating in the perinatal period(P27) | 36 | 1.7 | 7.6
9 | Influenza and pneumonia(J09–J18) | 32 | 1.5 | 6.8
10 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 25 | 1.2 | 5.3
… | All other causes(residual) | 718 | 34.0 | 151.7
| Postneonates, Black, non-Hispanic, male
… | All causes | 1,173 | 100.0 | 487.7
1 | Sudden infant death syndrome(R95) | 227 | 19.4 | 94.4
2 | Accidents (unintentional injuries)(V01–X59) | 209 | 17.8 | 86.9
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 130 | 11.1 | 54.0
4 | Assault (homicide)(*U01,X85–Y09) | 51 | 4.3 | 21.2
5 | Diseases of the circulatory system(I00–I99) | 50 | 4.3 | 20.8
6 | Diarrhea and gastroenteritis of infectious origin(A09) | 31 | 2.6 | 12.9
7 | Chronic respiratory disease originating in the perinatal period(P27) | 22 | 1.9 | 9.1
8 | Septicemia(A40–A41) | 21 | 1.8 | 8.7
9 | Influenza and pneumonia(J09–J18) | 19 | 1.6 | 7.9
9 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 19 | 1.6 | 7.9
… | All other causes(residual) | 394 | 33.6 | 163.8
| Postneonates, Black, non-Hispanic, female
… | All causes | 938 | 100.0 | 402.9
1 | Accidents (unintentional injuries)(V01–X59) | 171 | 18.2 | 73.4
2 | Sudden infant death syndrome(R95) | 167 | 17.8 | 71.7
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 133 | 14.2 | 57.1
4 | Diseases of the circulatory system(I00–I99) | 39 | 4.2 | 16.7
5 | Assault (homicide)(*U01,X85–Y09) | 27 | 2.9 | 11.6
6 | Septicemia(A40–A41) | 24 | 2.6 | 10.3
7 | Diarrhea and gastroenteritis of infectious origin(A09) | 20 | 2.1 | 8.6
8 | Chronic respiratory disease originating in the perinatal period(P27) | 14 | 1.5 | 6.0
9 | Influenza and pneumonia(J09–J18) | 13 | 1.4 | 5.6
10 | Volume depletion, disorders of fluid, electrolyte and acid–base balance(E86–E87) | §§ | §§ | §§
10 | Meningitis(G00,G03) | §§ | §§ | §§
… | All other causes(residual) | 314 | 33.5 | 134.9
| Postneonates, Native Hawaiian and Other Pacific Islander, non-Hispanic, both sexes
… | All causes | 36 | 100.0 | 347.0
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
2 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
3 | Sudden infant death syndrome(R95) | §§ | §§ | §§
4 | Diarrhea and gastroenteritis of infectious origin(A09) | §§ | §§ | §§
4 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
4 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
4 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
4 | Assault (homicide)(*U01,X85–Y09) | §§ | §§ | §§
… | All other causes(residual) | 10 | 27.8 | 96.4
| Postneonates, Native Hawaiian and Other Pacific Islander, non-Hispanic, male
… | All causes | 20 | 100.0 | 376.9
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
2 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
3 | Sudden infant death syndrome(R95) | §§ | §§ | §§
4 | Diarrhea and gastroenteritis of infectious origin(A09) | §§ | §§ | §§
4 | Influenza and pneumonia(J09–J18) | §§ | §§ | §§
4 | Newborn affected by maternal complications of pregnancy(P01) | §§ | §§ | §§
4 | Assault (homicide)(*U01,X85–Y09) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Postneonates, Native Hawaiian and Other Pacific Islander, non-Hispanic, female
… | All causes | 16 | 100.0 | 315.6
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | §§ | §§ | §§
1 | Accidents (unintentional injuries)(V01–X59) | §§ | §§ | §§
3 | Sudden infant death syndrome(R95) | §§ | §§ | §§
4 | Diseases of the circulatory system(I00–I99) | §§ | §§ | §§
… | All other causes(residual) | §§ | §§ | §§
| Postneonates, White, non-Hispanic, both sexes
… | All causes | 2,523 | 100.0 | 141.5
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 470 | 18.6 | 26.4
2 | Sudden infant death syndrome(R95) | 459 | 18.2 | 25.7
3 | Accidents (unintentional injuries)(V01–X59) | 419 | 16.6 | 23.5
4 | Diseases of the circulatory system(I00–I99) | 108 | 4.3 | 6.1
5 | Assault (homicide)(*U01,X85–Y09) | 62 | 2.5 | 3.5
6 | Septicemia(A40–A41) | 41 | 1.6 | 2.3
7 | Influenza and pneumonia(J09–J18) | 40 | 1.6 | 2.2
8 | Chronic respiratory disease originating in the perinatal period(P27) | 39 | 1.5 | 2.2
9 | Diarrhea and gastroenteritis of infectious origin(A09) | 36 | 1.4 | 2.0
10 | Malignant neoplasms(C00–C97) | 26 | 1.0 | 1.5
… | All other causes(residual) | 823 | 32.6 | 46.2
| Postneonates, White, non-Hispanic, male
… | All causes | 1,405 | 100.0 | 153.9
1 | Sudden infant death syndrome(R95) | 268 | 19.1 | 29.4
2 | Accidents (unintentional injuries)(V01–X59) | 236 | 16.8 | 25.8
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 232 | 16.5 | 25.4
4 | Diseases of the circulatory system(I00–I99) | 60 | 4.3 | 6.6
5 | Assault (homicide)(*U01,X85–Y09) | 35 | 2.5 | 3.8
6 | Influenza and pneumonia(J09–J18) | 27 | 1.9 | 3.0
7 | Diarrhea and gastroenteritis of infectious origin(A09) | 25 | 1.8 | 2.7
8 | Chronic respiratory disease originating in the perinatal period(P27) | 23 | 1.6 | 2.5
9 | Septicemia(A40–A41) | 19 | 1.4 | 2.1
10 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 14 | 1.0 | 1.5
… | All other causes(residual) | 466 | 33.2 | 51.0
| Postneonates, White, non-Hispanic, female
… | All causes | 1,118 | 100.0 | 128.5
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 238 | 21.3 | 27.4
2 | Sudden infant death syndrome(R95) | 191 | 17.1 | 22.0
3 | Accidents (unintentional injuries)(V01–X59) | 183 | 16.4 | 21.0
4 | Diseases of the circulatory system(I00–I99) | 48 | 4.3 | 5.5
5 | Assault (homicide)(*U01,X85–Y09) | 27 | 2.4 | 3.1
6 | Septicemia(A40–A41) | 22 | 2.0 | 2.5
7 | Chronic respiratory disease originating in the perinatal period(P27) | 16 | 1.4 | 1.8
8 | Malignant neoplasms(C00–C97) | 13 | 1.2 | 1.5
8 | Influenza and pneumonia(J09–J18) | 13 | 1.2 | 1.5
10 | Diarrhea and gastroenteritis of infectious origin(A09) | 11 | 1.0 | 1.3
… | All other causes(residual) | 356 | 31.8 | 40.9

†Based on number of deaths.

§ Data for age not stated are included in "all ages" but not distributed among age groups.

¶ Data for two or more races and origin not stated are included in "all races and origins" but are not distributed among race and Hispanic-origin groups. For the race and Hispanic-origin categories shown, only one race was reported on the death certificate.

** Percentages may not add to 100 because of rounding.

… Category not applicable.

§§ Estimate does not meet National Center for Health statistics standards of reliability.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

This report presents the 10 leading causes of death by age, race and Hispanic origin, and sex. Where shown in tables, the “All other causes (residual)” category refers to causes that were not ranked among the top 10 causes of death for a specified population, whether leading causes were derived from the 52 rankable causes in the “List of 113 Selected Causes of Death” or from the 71 rankable causes of the “List of 130 Selected Causes of Infant Death” mentioned previously.

### Age groupings

Leading causes of death for those age 1 year and older are presented in Table 1 for the following age categories: 1–4, 5–9, 10–14, 15–19, 20–24, 25–34, 35–44, 45–54, 55–64, 65 and older, 65–74, 75–84, and 85 and older. This set of age categories was adopted in 1999 in response to an increasing number of requests from data users for more age detail, and it represents a substantial expansion from the age categories previously used in these tables to present leading-cause data (11). In this report, a discussion of leading causes by age uses the following summary age categories: 1–9, 10–24, 25–44, 45–64, 65 and older, and 85 and older. Table 2, which presents data for infants (younger than age 1 year), also shows leading causes of death for the age subcategories neonatal (younger than 28 days) and postneonatal (28 days through 11 months).

The age grouping used when ranking causes of death can affect the rankings assigned to any particular age (12). For example, in 2024, the rankings for the 10 leading causes of death for a 45-year-old man were different depending on whether the ranking was based on the age group 45–49 or 45–54. In both age groups, unintentional injuries and heart disease are leading causes of death, but whereas unintentional injuries ranked as the top leading cause of death and heart disease followed in second place among men ages 45–49, the two conditions changed places (that is, heart disease is the first leading cause and unintentional injuries the second) when considering men ages 45–54. As a result, the relative importance of these two causes for men at or near age 45 changes depending on the age category selected.

### Data by race and Hispanic origin

Starting in 2018, all 50 states and D.C. reported race and Hispanic-origin data for the entire year using the 2003 revision of the U.S. Standard Certificate (13), which allowed for the collection of race data according to 1997 OMB standards (3). These standards require the collection, tabulation, and reporting of multiple races (any combination of two or more designated races) and use of a minimum of five single-race categories: American Indian and Alaska Native, Asian, Black or African American, Native Hawaiian and Other Pacific Islander, and White. The implementation of the revised death certificate was not completed by all vital statistics jurisdictions until data year 2018. In the interim, for the sake of uniformity and comparability of mortality data among jurisdictions, as well as with population estimates from the U.S. Census Bureau, multiple-race data were bridged (14) back to the four minimum, single-race categories of the 1977 OMB standards (15): American Indian and Alaska Native, Asian or Pacific Islander, Black, and White. Because the transition to the 2003 revision of the death certificate has been completed, bridged-race data will no longer be the basis for official mortality statistics as of data year 2018 but will be provided as supplemental information through data year 2020 to allow comparisons over time. For more details about the 2003 revision of the death certificate, delays in its implementation, and race bridging in deaths and population estimates, see “Deaths: Final Data for 2022” (5).

This report presents combined single-race and Hispanic-origin categories consistent with the 1997 OMB standards as: Hispanic; American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native); Asian non-Hispanic (subsequently, Asian); Black non-Hispanic (subsequently, Black); Native Hawaiian and Other Pacific Islander non-Hispanic (subsequently, Native Hawaiian and Other Pacific Islander); and White non-Hispanic (subsequently, White). Because the number of decedents for whom two or more races were reported is small (0.6% of deaths in 2024), multiple-race decedents are included in totals but are not distributed among race and Hispanic-origin categories. For details on the differences between bridged- and single-race mortality estimates, see “Comparability of Race-specific Mortality Data Based on 1977 Versus 1997 Reporting Standards” (4).

Race and Hispanic origin are reported separately on the death certificate; consequently, leading-cause data presented in this report for non-Hispanic decedents reflect a combination of these two characteristics. People of Hispanic origin may be of any race, and data are not tabulated by race in this report. Aggregated Hispanic-origin data are not affected by the transition to 1997 OMB standards. Because of net misclassification of race and Hispanic origin on the death certificate, deaths for the American Indian and Alaska Native population are estimated to be underreported by 34%, the Asian or Pacific Islander population by 3%, and the Hispanic-origin population by 3% (16,17). Consequently, data for these groups should generally be interpreted with caution. Although the findings on net misclassification noted are based on bridged-race mortality data, this report assumes that race is similarly misclassified in single-race data because the data collection process for race has not changed. Although a recent report found some variation in cause-of-death misclassification for the American Indian and Alaska Native population (17), this is unlikely to significantly affect the cause-of-death rankings for the race and Hispanic-origin groups, or hinder comparisons of relative mortality burden across groups.

## Results

In 2024, the 10 leading causes of death accounted for 70.9% of all deaths occurring in the United States (Table C). The 1st and 2nd leading causes of death, Diseases of heart (heart disease) and Malignant neoplasms (cancer), respectively, together accounted for 42.4% of all deaths in 2024. Accidents (unintentional injuries) ranked 3rd, accounting for 6.4% of all deaths. Cerebrovascular diseases (stroke) ranked 4th and Chronic lower respiratory diseases ranked 5th; these causes accounted for 5.4% and 4.7% of all deaths, respectively. Completing the top 10 for 2024 were Alzheimer disease (6th); Diabetes mellitus (diabetes) (7th); Nephritis, nephrotic syndrome and nephrosis (kidney disease) (8th); Chronic liver disease and cirrhosis (liver disease) (9th), and suicide (10th). These five causes together accounted for 12.0% of deaths in 2024.

Table C Deaths and percentage of total deaths for the 10 leading causes of death: United States, 2023 and 2024

[An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10)]

Cause of death (based on ICD–10) | 2024 | | | 2023
Cause of death (based on ICD–10) | Rank^†^ | Deaths | Percent of total deaths | Rank^†^ | Deaths | Percent of total deaths
All causes | … | 3,072,666 | 100.0 | … | 3,090,964 | 100.0
Diseases of heart(I00–I09,I11,I13,I20–I51) | 1 | 683,491 | 22.2 | 1 | 680,981 | 22.0
Malignant neoplasms(C00–C97) | 2 | 619,876 | 20.2 | 2 | 613,352 | 19.8
Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3 | 197,449 | 6.4 | 3 | 222,698 | 7.2
Cerebrovascular diseases(I60–I69) | 4 | 166,852 | 5.4 | 4 | 162,639 | 5.3
Chronic lower respiratory diseases(J40–J47) | 5 | 145,643 | 4.7 | 5 | 145,357 | 4.7
Alzheimer disease(G30) | 6 | 116,022 | 3.8 | 6 | 114,034 | 3.7
Diabetes mellitus(E10–E14) | 7 | 94,445 | 3.1 | 7 | 95,190 | 3.1
Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 8 | 55,081 | 1.8 | 8 | 55,253 | 1.8
Chronic liver disease and cirrhosis(K70,K73–K74) | 9 | 52,274 | 1.7 | 9 | 52,222 | 1.7
Intentional self–harm (suicide)(*U03,X60–X84,Y87.0) | 10 | 48,824 | 1.6 | 11 | 49,316 | 1.6
COVID-19 U07.1) | 15 | 31,426 | 1.0 | 10 | 49,932 | 1.6

†Based on number of deaths.

…Category not applicable.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

The ranked order of one of the 10 leading causes in 2024 changed compared with 2023 (18). Intentional self-harm (suicide) moved up to 10th place in 2024, from 11th in 2023. All causes that were previously ranked 1st–9th maintained their respective positions in 2024.

From 2023 to 2024, the number of deaths decreased for 5 of the 10 leading causes of death (Table C). The largest decline was for COVID-19, 37% lower in 2024 (31,426) than in 2023 (49,932). Declines in the number of deaths for other causes were: unintentional injuries by 11.3%, diabetes by 0.8%, kidney disease by 0.3%, and suicide by 1.0%. The number of cancer deaths increased 1.1%, from 613,352 in 2023 to 619,876 in 2024.

### Differences by sex

Males and females shared 8 of the 10 leading causes of death, with identical rankings for 3 of these causes. For both populations, heart disease and cancer ranked as the first and second leading causes of death, respectively (Figure 1, Table 1). In 2024, heart disease accounted for 23.6% of all deaths among males and 20.8% of all deaths among females. The percentage of all deaths attributable to cancer was essentially the same for males and females, 20.4% and 20.0%, respectively. Another leading cause of death with the same rank for males and females was Chronic lower respiratory diseases, ranked fifth. However, the burden of deaths from this cause was higher for females (5.3% of all deaths) than males (4.2%).

Figure 1 Percent distribution of the 10 leading causes of death, by sex: United States, 2024

* CLRD is Chronic lower respiratory diseases.

NOTE: Values show percentage of total deaths.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 1 shows two bar charts of the percent distribution of the 10 leading causes of death by sex in the United States in 2024.

Males and females differed in the ranking of other causes of death. In 2024, males had a higher relative burden of mortality from unintentional injuries, which was the third leading cause of death for this group, accounting for 8.1% of deaths (Figure 1, Table 1). It was the sixth leading cause for females, accounting for 4.6% of deaths. Males had a lower relative burden of mortality from stroke, which ranked fourth and accounted for 4.6% of all male deaths but ranked third and accounted for 6.4% of all female deaths. Diabetes ranked sixth for males but seventh for females, accounting for 3.4% and 2.7% of all deaths, respectively. Alzheimer disease ranked eighth for males, accounting for 2.3% of deaths, but it ranked fourth for females, accounting for 5.3% of deaths. Although kidney disease ranked lower for males (10th) than females (8th), it accounted for the same percentage of deaths for both: 1.8%.

Additionally, 3 of the 10 leading causes of death were unique to either population in 2024. Suicide ranked 7th for males (2.4% of deaths) but was not ranked among the 10 leading causes for females. Chronic liver disease and cirrhosis was the 9th leading cause for males (2.0% of deaths), but it was not in the top 10 for females. Hypertensive disease ranked 10th for females (1.5% of deaths) but was not among the 10 leading causes of death for males.

Compared with 2023, all leading causes for males stayed the same rank in 2024 (18), whereas for females, nine causes retained their 2023 rank. Influenza and pneumonia moved up from 11th to 9th place, and COVID-19 moved down in rank from 9th to 15th place. The 10th leading cause in 2023 (Hypertension) remained in that spot for 2024.

### Differences by age

Differing patterns in the leading causes of death were observed by age group, although all groups shared three of the leading causes: heart disease, cancer, and unintentional injuries (Figure 2). Generally, for younger age groups, external causes (unintentional injuries, suicide, and homicide) accounted for more deaths than other causes, whereas for older age groups, chronic diseases were more prevalent. In 2024, the leading cause of death (first) for the population ages 1–44 was unintentional injuries. The relative burden of mortality from this cause was greater in this age range, accounting for 37.5% of deaths for age group 10–24, 33.6% for 25–44, and 30.9% for 1–9. In contrast, unintentional injuries was the third leading cause of death for age group 45–64 (10.4% of deaths) and sixth for 65 and older (3.2%) and 85 and older (3.1%). For the population ages 45–64, the leading cause of death was cancer, accounting for 25.4% of deaths. Cancer was the second leading cause of death for those age 65 and older (20.1%), 85 and older (11.9%), and children ages 1–9 (10.6%); the third among adults ages 25–44 (9.8%); and the fourth among those ages 10–24 (5.6%). Heart disease was the leading cause of death among adults age 65 and older, accounting for 24.0% of deaths, and it remained the leading cause among those 85 and older (27.3%). In contrast, heart disease ranked as the fifth leading cause among children ages 1–9 (3.4%) and 10–24 (2.8%), the fourth leading cause among adults ages 25–44 (9.7%), and the second leading cause among those 45–64 (20.6%).

Figure 2 Percent distribution of the 10 leading causes of death, by age group: United States, 2024

* CLRD is Chronic lower respiratory diseases.

NOTES: Values show percentage of total deaths. Numbers may not add to 100% due to rounding.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 2 shows six bar charts of the percent distribution of the 10 leading causes of death by age group for ages 1–9, 10–24, 25–44, 45–64, 65 and over, and 85 and over in the United States in 2024.

Stroke ranked in the top 10 leading causes for all age groups, although its rank and burden of mortality were higher at older ages. Stroke ranked third for those age 65 and older (6.2%) and 85 and older (7.7%). Stroke ranked sixth for age group 45–64 (3.6%), seventh for 1–9 (1.7%), and eighth for 25–44 (1.7%).

Diabetes was among the 10 leading causes of death for all age groups except 1–9, with the highest rank and burden of disease for those ages 45–64 (fifth, accounting for 4.3% of deaths). Chronic lower respiratory diseases ranked among the 10 leading causes for all age groups except 25–44, with its highest rank of fourth for those 65 and older (5.4%).

For the population ages 10–64, suicide was among the 10 leading causes of death: It was the second leading cause of death for age groups 10–24 (19.2% of deaths) and 25–44 (10.6%), and eighth for 45–64 (3.0%). Homicide was among the 10 leading causes of death for ages 1–44, ranking fourth for age group 1–9 (6.5% of deaths), third for 10–24 (15.1%), and fifth for 25–44 (5.8%).

Influenza and pneumonia ranked sixth for children ages 1–9 and ninth for age groups 10–24 and 25–44, but it was not ranked among the 10 leading causes for 45–64. Kidney disease ranked 8th or 9th for all age groups 35 and older but was not among the top 10 leading causes at younger ages.

Some causes of death were concentrated in just a few age groups. Congenital malformations, deformations and chromosomal abnormalities (congenital malformations) was the third leading cause for children ages 1–9 (9.8% of deaths) and sixth for age group 10–24 (2.0%), but it was not among the 10 leading causes for age groups 25 and older. For those ages 25–44 and 45–64, liver disease was ranked sixth (4.3% of deaths) and fourth (4.4%), respectively, but was not among the 10 leading causes of death for the other age groups.

Alzheimer disease was one of the leading causes of death at the oldest ages, ranking fourth for those age 85 and older (7.6% of deaths) and fifth for those age 65 and older (4.9%). It was not one of the 10 leading causes for those 64 and younger.

Influenza and pneumonia ranked as the 10th leading cause of death among adults age 65 and older (1.7%) and as the 9th leading cause among those 85 and older (1.8%).

Some notable changes in the ranking of the leading causes of death were observed across age groups from 2023 to 2024. COVID‑19 dropped in rank for people age 65 and older, with the largest decline of 37% among those 85 and older. This decline in COVID‑19 deaths contributed to shifts in the ranking of other causes of death for the other age groups in 2024.

### Differences by race and Hispanic origin

Table D shows variation across six race and Hispanic-origin groups in the top 10 leading causes of death in 2024. Deaths for the Hispanic population and for non-Hispanic populations other than White and Black are underreported to varying degrees on the death certificate (5,16). The six groups shared six of the 10 leading causes but had different relative disease burdens.

Heart disease was the first leading cause of death for all groups with the exception of the Asian and Hispanic populations, where it was the second leading cause (Table D). The burden of mortality from heart disease was relatively similar for the Black and White populations, accounting for 22.8% and 22.7%, respectively, of all deaths. Among the six race and Hispanic-origin groups, heart disease accounted for the smallest percentage of deaths for the American Indian and Alaska Native population (17.6%).

Table D Deaths and percentage of total deaths for the 10 leading causes of death, by race and Hispanic origin: United States, 2024

[Race and Hispanic-origin categories are consistent with 1997 Office of Management and Budget standards. Race and Hispanic origin are reported separately on the death certificate. People of Hispanic origin may be of any race. Data for Hispanic people are not tabulated by race; data for non-Hispanic people are tabulated by race. Data for racial and ethnic groups other than non-Hispanic White and non-Hispanic Black should be interpreted with caution because of misreporting of Hispanic origin and race on the death certificate. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10)]

Cause of death (based on ICD–10) | Hispanic | | | Non-Hispanic, single race
Cause of death (based on ICD–10) | Hispanic | | | American Indian and Alaska Native | | | Asian | | | Black | | | Native Hawaiian and Other Pacific Islander | | | White
Cause of death (based on ICD–10) | Rank^†^ | Deaths | Percent of total deaths | Rank^†^ | Deaths | Percent of total deaths | Rank^†^ | Deaths | Percent of total deaths | Rank^†^ | Deaths | Percent of total deaths | Rank^†^ | Deaths | Percent of total deaths | Rank^†^ | Deaths | Percent of total deaths
All causes | … | 260,799 | 100.0 | … | 20,924 | 100.0 | … | 87,728 | 100.0 | … | 380,945 | 100.0 | … | 4,431 | 100.0 | … | 2,290,348 | 100.0
Malignant neoplasms(C00–C97) | 1 | 51,120 | 19.6 | 2 | 3,229 | 15.4 | 1 | 20,575 | 23.5 | 2 | 72,666 | 19.1 | 2 | 913 | 20.6 | 2 | 466,773 | 20.4
Diseases of heart(I00–I09,I11,I13,I20–I51) | 2 | 47,679 | 18.3 | 1 | 3,688 | 17.6 | 2 | 17,742 | 20.2 | 1 | 86,693 | 22.8 | 1 | 1,035 | 23.4 | 1 | 520,559 | 22.7
Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 3 | 26,105 | 10.0 | 3 | 2,704 | 12.9 | 4 | 4,228 | 4.8 | 3 | 28,556 | 7.5 | 3 | 309 | 7.0 | 3 | 132,227 | 5.8
Cerebrovascular diseases(I60–I69) | 4 | 14,629 | 5.6 | 7 | 782 | 3.7 | 3 | 6,662 | 7.6 | 4 | 22,946 | 6.0 | 5 | 267 | 6.0 | 5 | 120,457 | 5.3
Diabetes mellitus(E10–E149) | 5 | 12,070 | 4.6 | 5 | 1,104 | 5.3 | 5 | 3,865 | 4.4 | 5 | 16,674 | 4.4 | 4 | 295 | 6.7 | 7 | 59,490 | 2.6
Alzheimer disease(G30) | 6 | 9,296 | 3.6 | 10 | 365 | 1.7 | 6 | 3,425 | 3.9 | 9 | 8,881 | 2.3 | 9 | 81 | 1.8 | 6 | 93,490 | 4.1
Chronic liver disease and cirrhosis(K70,K73–K74) | 7 | 8,724 | 3.3 | 4 | 1,287 | 6.2 | 15 | 924 | 1.1 | 14 | 3,701 | 1.0 | 13 | 53 | 1.2 | 8 | 37,036 | 1.6
Chronic lower respiratory diseases(J40–J47) | 8 | 5,709 | 2.2 | 6 | 829 | 4.0 | 9 | 1,843 | 2.1 | 6 | 11,374 | 3.0 | 7 | 98 | 2.2 | 4 | 124,575 | 5.4
Intentional self–harm (suicide)(*U03,X60–X84,Y87.0) | 9 | 5,382 | 2.1 | 8 | 545 | 2.6 | 11 | 1,508 | 1.7 | 13 | 3,795 | 1.0 | 8 | 96 | 2.2 | 9 | 36,560 | 1.6
Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 10 | 5,255 | 2.0 | 9 | 384 | 1.8 | 8 | 1,961 | 2.2 | 7 | 10,601 | 2.8 | 6 | 142 | 3.2 | 10 | 36,364 | 1.6
Influenza and pneumonia(J09–J18) | 11 | 4,481 | 1.7 | 11 | 356 | 1.7 | 7 | 2,026 | 2.3 | 12 | 5,642 | 1.5 | 11 | 77 | 1.7 | 11 | 35,101 | 1.5
Essential hypertension and hypertensive renal disease(I10,I12,I15) | 12 | 3,803 | 1.5 | 14 | 227 | 1.1 | 10 | 1,830 | 2.1 | 10 | 7,542 | 2.0 | 10 | 78 | 1.8 | 13 | 28,544 | 1.2
Assault (homicide)(*U01–*U02.9,X85–Y09,Y87.1) | 13 | 3,776 | 1.4 | 12 | 324 | 1.5 | 22 | 278 | 0.3 | 8 | 10,294 | 2.7 | 14 | 41 | 0.9 | 21 | 5,070 | 0.2

†Based on number of deaths. Ranks above 10 are provided for informational purposes when a cause is among the top 10 for at least one of the groups being compared.

… Category not applicable.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

The Asian and Hispanic populations had cancer as the leading cause, with Asian people having the highest burden of mortality from cancer of any group, accounting for 23.5% of all deaths. Cancer ranked second for all other race and Hispanic-origin groups, with American Indian and Alaska Native populations having the lowest percentage of deaths due to cancer (15.4%).

Unintentional injuries ranked third for all groups except the Asian population, where it ranked fourth. The American Indian and Alaska Native population had the highest percentage of deaths of any group attributable to this cause (12.9%) and the Asian population had the lowest (4.8%).

Stroke, diabetes, Alzheimer disease, and Chronic lower respiratory diseases also ranked among the top 10 causes of death for each race and Hispanic-origin group. Stroke ranked third for the Asian population (7.6% of deaths), fourth for the Black (6.0%) and Hispanic (5.6%) populations, fifth for the Native Hawaiian and Other Pacific Islander (6.0%) and White (5.3%) populations, and seventh for the American Indian and Alaska Native population (3.7%).

Diabetes ranked fourth for the Native Hawaiian and Other Pacific Islander population; fifth for the Asian, American Indian and Alaska Native, Black, and Hispanic populations; and seventh for the White population. The percentage of deaths attributable to diabetes was highest for the Native Hawaiian and Other Pacific Islander population (6.7%) and lowest for the White population (2.6%).

Chronic lower respiratory diseases ranked fourth for the White population, sixth for the American Indian and Alaska Native population, seventh for the Native Hawaiian and Other Pacific Islander and Black populations, eighth for the Hispanic population, and ninth for the Asian population. The percentage of all deaths attributable to Chronic lower respiratory diseases ranged from 5.4% for White people to 2.1% for Asian people.

Some of the top 10 leading causes were shared by some groups but not by others. Alzheimer disease ranked 6th for the Hispanic, Asian, and White populations and 9th for the Native Hawaiian and Other Pacific Islander and Black populations, but it was not one of the 10 leading causes of death in 2024 for the American Indian and Alaska Native population. Chronic liver disease and cirrhosis ranked 4th for the American Indian and Alaska Native population, 7th for the Hispanic population, and 8th for the White population, but it was not one of the leading causes for the other groups. Suicide ranked 8th for the Native Hawaiian and Other Pacific Islander and American Indian and Alaska Native populations and 9th for the Hispanic and White populations. Influenza and pneumonia ranked among the top 10 causes of death for only the Asian population (7th). Essential hypertension ranked among the top 10 only for the Asian, Black, and Native Hawaiian and Other Pacific Islander populations (10th for each). Homicide ranked in the top 10 leading causes only for the Black population (8th).

All groups experienced changes in the leading-cause rankings from 2023 to 2024 (17). Only Hispanic people experienced a change in the top leading cause, from heart disease in 2023 to cancer in 2024. Other changes, partly attributable to COVID-19 dropping in rank, were noted for all groups.

### Leading causes of infant death

The leading cause of infant death in 2024 was congenital malformations, which accounted for 20.3% of all infant deaths (Table E). The 2nd leading cause was Disorders related to short gestation and low birth weight, not elsewhere classified (low birth weight) (14.7% of deaths). Sudden infant death syndrome ranked 3rd and accounted for 6.7% of deaths. Unintentional injuries ranked 4th (6.2% of deaths), and Newborn affected by maternal complications of pregnancy (maternal complications) ranked 5th (6.0%). In 2024, more than one-half of infant deaths were attributable to these five leading causes (53.8%). Other leading causes in 2024 were: Bacterial sepsis of newborn (6th); Newborn affected by complications of placenta, cord and membranes (7th); Respiratory distress of newborn (8th); Diseases of the circulatory system (9th); and Intrauterine hypoxia and birth asphyxia (10th). Together, these 10 leading causes of infant death accounted for nearly two-thirds of all infant deaths (65.8%).

Table E Deaths and percentage of total deaths for the 10 leading causes of infant death: United States, 2024 and 2023

Cause of death (based on the International Classification of Diseases, 10th Revision) | 2024 | | | 2023
Cause of death (based on the International Classification of Diseases, 10th Revision) | Rank^*^ | Deaths | Percent of total deaths | Rank^*^ | Deaths | Percent of total deaths
All causes | … | 20,050 | 100.0 | … | 20,145 | 100.0
Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 1 | 4,061 | 20.3 | 1 | 4,005 | 19.9
Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 2 | 2,941 | 14.7 | 2 | 2,922 | 14.5
Sudden infant death syndrome(R95) | 3 | 1,351 | 6.7 | 3 | 1,445 | 7.2
Accidents (unintentional injuries)(V01–X59) | 4 | 1,245 | 6.2 | 4 | 1,291 | 6.4
Newborn affected by maternal complications of pregnancy(P01) | 5 | 1,193 | 6.0 | 5 | 1,141 | 5.7
Bacterial sepsis of newborn(P36) | 6 | 603 | 3.0 | 6 | 621 | 3.1
Newborn affected by complications of placenta, cord and membranes(P02) | 7 | 594 | 3.0 | 7 | 569 | 2.8
Respiratory distress of newborn(P22) | 8 | 453 | 2.3 | 8 | 449 | 2.2
Diseases of the circulatory system(I00–I99) | 9 | 376 | 1.9 | 10 | 356 | 1.8
Intrauterine hypoxia and birth asphyxia(P20–P21) | 10 | 368 | 1.8 | 9 | 365 | 1.8

* Based on number of deaths.

… Category not applicable.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

The only change in the ranked order of the leading causes of infant death from 2023 to 2024 was that Diseases of the circulatory system and Intrauterine hypoxia and birth asphyxia exchanged positions, ranking 9th and 10th, respectively.

### Neonatal and postneonatal mortality

Differences were evident when comparing leading causes of death in the neonatal (younger than 28 days after birth) and postneonatal (from 28 days through 11 months after birth) periods (Table F). Congenital malformations was the leading cause of neonatal death in 2024. In contrast, Sudden infant death syndrome was the leading cause of postneonatal death. Congenital malformations ranked first for neonates and second for postneonates. The remaining leading causes of neonatal death were characterized by conditions occurring in the perinatal period, while in the postneonatal period the remaining leading causes included several conditions prevalent among the general population. These included unintentional injuries (ranked third), homicide (fifth), Septicemia (seventh), and Influenza and pneumonia (ninth).

Table F Deaths and percentage of total deaths for the 10 leading causes and all other causes of neonatal and postneonatal deaths: United States, 2024

[Neonatal deaths are those occurring less than 28 days after birth. Postneonatal deaths are those occurring from 28 days through 11 months after birth. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10)]

Rank^†^ | Cause of death (based on ICD–10) | Deaths | Percent of total deaths^§^
| Neonatal
… | All causes | 13,246 | 100.0
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 2,876 | 21.7
2 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 2,867 | 21.6
3 | Newborn affected by maternal complications of pregnancy(P01) | 1,177 | 8.9
4 | Newborn affected by complications of placenta, cord and membranes(P02) | 586 | 4.4
5 | Bacterial sepsis of newborn(P36) | 578 | 4.4
6 | Respiratory distress of newborn(P22) | 441 | 3.3
7 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 358 | 2.7
8 | Neonatal hemorrhage(P50–P52,P54) | 332 | 2.5
9 | Necrotizing enterocolitis of newborn(P77) | 286 | 2.2
10 | Atelectasis(P28.0–P28.1) | 273 | 2.1
… | All other causes (residual) | 3,472 | 26.2
| Postneonatal
… | All causes | 6,804 | 100.0
1 | Sudden infant death syndrome(R95) | 1,215 | 17.9
2 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 1,185 | 17.4
3 | Accidents (unintentional injuries)(V01–X59) | 1,081 | 15.9
4 | Diseases of the circulatory system(I00–I99) | 293 | 4.3
5 | Assault (homicide)(*U01,X85–Y09) | 219 | 3.2
6 | Diarrhea and gastroenteritis of infectious origin(A09) | 141 | 2.1
7 | Septicemia(A40–A41) | 121 | 1.8
8 | Chronic respiratory disease originating in the perinatal period(P27) | 116 | 1.7
9 | Influenza and pneumonia(J09–J18) | 99 | 1.5
10 | Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 74 | 1.1
… | All other causes(residual) | 2,260 | 33.2

†Based on number of deaths.

§ Percentages may not add to 100 due to rounding.

… Category not applicable.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

The ranked order for 6 of the top 10 leading causes of neonatal death in 2024 remained the same as in 2023, while Congenital malformations moved up as the first leading cause; Conditions originating in the perinatal period moved down to second; Newborn affected by complications of placenta, cord and membranes moved up from fifth to fourth; and Bacterial sepsis of newborn moved down from fourth to fifth position.

For postneonatal deaths, 3 of the 10 leading causes changed rank in 2024. Influenza and pneumonia dropped from sixth in 2023 to ninth in 2024, Diarrhea and gastroenteritis of infectious origin rose from eighth to sixth, and Chronic respiratory disease originating in the perinatal period increased from ninth to eighth (18).

Differences in infant mortality, including neonatal and postneonatal mortality, by race and Hispanic origin are detailed in Table 2. However, these differences are not discussed. Race reported on the death certificate is considered to be fairly accurate for White and Black infants; however, both race and Hispanic origin may be misreported for other groups (16,17,19–22). Consequently, readers are directed to a report using data from the linked file of live births and infant deaths for better measures of infant mortality by race and Hispanic origin (23).

## Discussion

Changes in the top 10 leading causes of death were observed for some demographic groups from 2023 to 2024. The leading causes of death for the Hispanic population between 2023 and 2024 remained the same. COVID-19 dropped in rank for all race and Hispanic-origin groups and dropped off of the top 10 leading causes of death in 2024. COVID-19 also dropped in rank for all age groups and was only in the top 10 leading causes of death for age groups 65 and older and 85 and older. For the total population, the number of deaths increased for 6 of the 10 leading causes of death between 2023 and 2024. The top 10 leading causes of death in 2024 remained unchanged for the Hispanic population. Among the Black, Native Hawaiian and Other Pacific Islander, and American Indian and Alaska Native populations, Chronic lower respiratory diseases moved up one ranked position—to sixth, seventh, and ninth, respectively—while rankings for the remaining population groups did not change. These shifts reflect differences in the relative burden of other leading causes of death across population groups and demonstrate how rankings may vary by race and Hispanic origin.

This report presents the top 10 leading causes of death in the United States by age, sex, race, and Hispanic origin, and for the infant, neonatal, and postneonatal periods. Cause-of-death ranking is a standard method of presenting mortality statistics and is a useful tool for illustrating the relative burden of cause-specific mortality, but it must be used cautiously and with a clear understanding of the limitations underlying the method.

When comparing rankings across demographic groups or over time, note the age distribution of the populations being compared. Leading causes of death for populations with younger age distributions will tend to show higher rankings for causes of death that are prevalent among younger people, such as unintentional injuries, homicide, and suicide. Leading causes for older populations will tend to show higher rankings for causes that are more prevalent among older people, such as heart disease, cancer, Alzheimer disease, and stroke. In addition, the changes to race and ethnicity classification starting in 2018 should be noted when analyzing the changes in rank over time by race and Hispanic origin (4,18).

Consideration should also be given to the effects of random variation on cause-of-death rankings. When the number of events is small (perhaps fewer than 100 deaths), estimates of mortality risk are subject to random fluctuations; see Technical Notes. Especially when comparing rankings based on small numbers of deaths between groups or over time, be aware that differences in relative rankings may be attributable to random variability.

Because the ranked order of any particular cause of death will depend on the list of causes from which selection is made and on the rules applied in making the selection, a clearly defined and uniform method for ranking causes of death is vital to maintain consistency in the reporting of leading causes by federal and state agencies. The standard method and cause lists described in this and other publications (1,2,5,8) provide this structure.

## Acknowledgments

This report was prepared in the Division of Vital Statistics under the general direction of Paul D. Sutton, Director, Division of Vital Statistics; Robert N. Anderson, Chief, Statistical Analysis and Surveillance Branch; and Elizabeth Arias, Team Leader, Mortality Statistics and Research Team (MSRT). Sherry L. Murphy of MSRT contributed to the Technical Notes. Jiaquan Xu of MSRT provided content and table review. Registration Methods staff and staff of the Data Acquisition, Classification, and Evaluation Branch provided consultation to state vital statistics offices regarding the collection of the death certificate data on which this report is based. The National Center for Health Statistics Office of Information Services, Information Design and Publishing Staff produced this report: editor Laura Drescher and typesetter and graphic designer Simon McCann.

## Technical Notes

### Data

Data in this report are based on information from all death certificates that were filed in the 50 states and the District of Columbia in 2024 and processed by the National Center for Health Statistics (NCHS) through the Vital Statistics Cooperative Program. For details about the nature and sources of data, revision of the U.S. Standard Certificate of Death, and terrorism-related deaths, see Technical Notes of the companion report, “Deaths: Final Data for 2024” (5). The mortality statistics in this report include deaths for U.S. residents only.

### Cause-of-death classification

The mortality statistics presented in this report were compiled according to World Health Organization (WHO) regulations, which specify that member nations classify and code causes of death in according to the current revision of the International Statistical Classification of Diseases and Related Health Problems (ICD). ICD provides the basic guidance used in virtually all countries to code and classify causes of death. Effective with deaths occurring in 1999, the United States began using the 10th revision of this classification, ICD–10 (6).

ICD not only details disease classification but also provides definitions, tabulation lists, the format of the death certificate, and the rules for coding cause of death. Cause-of-death data presented in this publication were coded by procedures outlined in annual issues of the NCHS Instruction Manual (8,24–28). The manual includes rules for selecting the underlying cause of death for tabulation purposes, definitions, tabulation lists, and regulations on the use of the classification.

Before 1968, mortality medical data were based on manual coding of an underlying cause of death for each certificate according to WHO rules. Effective with data year 1968, NCHS converted to computerized coding of the underlying cause and manual coding of all causes (multiple causes) on the death certificate. In this system, called Automated Classification of Medical Entities (ACME) (28), multiple-cause codes serve as inputs to computer software that use WHO rules to select the underlying cause. All cause-of-death data in this report were coded using ACME.

ACME is used to select the underlying cause of death for all death certificates in the United States. Additionally, NCHS developed two computer systems as inputs to ACME. Beginning with 1990 data, the Mortality Medical Indexing, Classification, and Retrieval (MICAR) system (29,30) was introduced to automate coding multiple causes of death. In addition, MICAR provided more detailed information on the conditions reported on death certificates than is available through the ICD code structure. An enhancement of the MICAR system, SuperMICAR, was introduced beginning with data year 1993 (31). SuperMICAR allowed for literal entry of the multiple cause-of-death text as reported by the certifier. This information was then processed automatically by MICAR and ACME. Records that could not be processed automatically by MICAR were manually coded for multiple cause and then further processed through ACME to determine underlying cause. SuperMICAR was last used to process the nation’s death records in 2021.

In 2022, NCHS began using MedCoder, a new system that integrates natural language processing and machine learning for coding multiple causes of death. This system replaced the Mortality Medical Data System (MMDS). MedCoder can code nearly 90% of records automatically, compared with less than 75% for the previous system. Implementation of MedCoder resulted in improvements in cause-of-death coding. Under the MMDS system, Ischemic stroke had been incorrectly coded to I64, Stroke unspecified, but is coded correctly to I63.9, Cerebral infarction unspecified, using the MedCoder system. For more information about MedCoder, visit MedCoder ( https://www.cdc.gov/nchs/nvss/medcoder.htm).

In this report, tabulations of cause of death statistics are based solely on the underlying cause of death. The underlying cause is defined by WHO as “the disease or injury which initiated the train of morbid events leading directly to death, or the circumstances of the accident or violence that produced the fatal injury” (6). The underlying cause is selected from the conditions entered by the physician or other medical certifier in the cause-of-death section of the death certificate. When more than one cause or condition is entered by the certifier, the underlying cause is determined by the sequence of conditions on the certificate, provisions of ICD, and associated selection rules and modifications. Generally, more medical information is reported on death certificates than is directly reflected in the underlying cause of death. This information is captured in NCHS multiple cause-of-death statistics (32–34).

### Coding changes in 2024

Effective with data year 2020, ICD–10 code U07.1 (COVID-19) was added as a new, valid, underlying cause-of-death code. See more information on COVID-19 as a cause of death in the COVID-19 section that follows. In 2024, no codes were added or deleted from the list of valid underlying cause of death. Information on the addition of U07.1 and codes added or deleted in previous years is available from: https://www.cdc.gov/nchs/data/dvs/Part9InstructionManual2020-508.pdf (5,8).

### COVID-19

COVID-19 (ICD–10 code U07.1) became an official new cause of death in 2020 after the first death from COVID-19 was reported in the United States (5,8). For people older than 1 year, COVID-19 was added as a rankable cause of death. For infants (younger than 1 year), COVID-19 was added to the cause-of-death category “Other and unspecified viral diseases” but is not considered as a separate rankable cause.

Deaths assigned to COVID-19 may not reflect all deaths directly or indirectly due to COVID-19 because some deaths due to COVID-19 may not have been diagnosed, especially early in the pandemic, and some deaths may have been assigned to another coexisting condition. COVID-19 data in this report do not include deaths where COVID-19 may have been reported as a contributing cause but was not considered to be the underlying cause of death. For additional coding detail and guidelines, see “Reporting and Coding Deaths Due to COVID-19 (https://www.cdc.gov/nchs/covid19/coding-and-reporting.htm).”

### Age

Decedents for whom age was not stated are included in total categories for “all ages” but are not distributed across age groups. Age was not stated for 57 decedents in 2024, 0.002% of all deaths. Age information was stated for all infants in 2024.

### Race and Hispanic origin

Demographic information on decedents, including race and Hispanic origin, is usually collected from informants and reported on death certificates by funeral directors. Race and Hispanic origin are reported separately on the death certificate but are shown combined in this report. Data shown for Hispanic people include all people of Hispanic origin of any race. In 2024, death records with race not stated or not classifiable (0.3% of all records) were imputed to one of the five single-race categories by assigning the record a single-race value based on the last single-race record processed. Records with Hispanic origin not stated or not classifiable were not imputed and accounted for 0.3% of all records.

For more details about race and Hispanic origin, including changes in the standards for classifying race and ethnicity, race bridging of deaths, the full implementation of the revised death certificate consistent with 1997 Office of Management and Budget (OMB) standards beginning with 2018 mortality data, and the quality of reporting on death certificates and surveys, see Technical Notes of “Deaths: Final Data for 2023” (5). For detailed comparisons between bridged-race and unbridged single-race data, see “Comparability of Race-specific Mortality Data Based on 1977 Versus 1997 Reporting Standards” (4).

Infant deaths were tabulated by race and Hispanic origin of the decedent. Live births, the denominators of infant mortality rates, were tabulated by race and Hispanic origin of the mother. In computing infant mortality rates, deaths and live births of unknown origin are not distributed among the specified Hispanic and non-Hispanic groups. The percentage of infant deaths of unknown origin was 1.2%, and the percentage of live births to mothers of unknown origin was 1.0% for the United States in 2024 (5,35). Infant mortality rates by specified race and Hispanic origin are more accurate when based on the linked file of infant deaths and live births (23). The linked file computes infant mortality rates using the race and Hispanic origin of the mother from the birth certificate in both the numerator and denominator. Race and Hispanic origin on the birth certificate are considered to be more accurate than on the death certificate. For more details, see “Deaths: Final Data for 2024” (5).

### Computation of rates and population bases

Rates in this report (except for infant mortality rates) are crude death rates presented per 100,000 estimated population in a specified group. Population estimates represent the population at risk of dying in a specified group. Population estimates for 2024 are estimated as of July 1, 2024, based on the blended base produced by the U.S. Census Bureau instead of the April 1, 2020, decennial population count. The blended base consists of the blend of Vintage 2020 postcensal population estimates, 2020 Demographic Analysis Estimates, and 2020 Census PL 94-171 Redistricting File (see “Methodology for the United States Population Estimates: Vintage 2024 (https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2024/methods-statement-v2024.pdf)”).

Beginning with 2023 data, NCHS implemented new statistical standards for the presentation of death rates and counts (36). For information on the new statistical methods used to determine whether death rates should be presented or suppressed, see “Implementation of New Data Presentation Standards for Rates and Counts for Mortality” (37).

The single-race estimates based on the 1997 OMB standards are available directly from the U.S. Census Bureau (38). For more details about changes in the standards for classifying race and ethnicity, the related race bridging of population estimates, and the full transition to estimates consistent with 1997 OMB standards as of data year 2018, see “Deaths: Final Data for 2023” (5).

Single-race population estimates used for this report are shown by race and Hispanic origin, sex, and age in the Table. The estimation procedures used to develop these populations are subject to error. Smaller populations (for example, American Indian and Alaska Native) are likely to be affected much more than larger populations (14). Although the nature and magnitude of these errors are unknown, the potential for error should be noted when evaluating trends and differentials.

Infant mortality rates are the most commonly used index for measuring the risk of dying during the first year of life. Infant mortality rates use the number of live births to approximate the population at risk of dying before the first birthday. They are calculated by dividing the number of infant deaths in a calendar year by the number of live births registered for the same period and are presented as rates per 100,000 live births. Neonatal and postneonatal mortality rates are also calculated using live births in the denominator. For final birth figures used in the denominator for infant mortality rates, see “Births: Final Data for 2024” (39).

### Random variation

The mortality data presented in this report are not subject to sampling error. However, mortality data, even based on complete counts, may be affected by random variation. When the number of events is small (perhaps fewer than 100 deaths) and the probability of such an event is small, caution must be taken when interpreting mortality data. This is less problematic when analyzing the relative ranking of causes of death because the observed frequency of deaths for any particular cause is fixed for any given group in any given year, and the ranking is based on that fixed value. Despite this, when comparing rankings based on small numbers of deaths between demographic groups or over time, be aware that differences in relative rankings may be attributable to random variability (see reference 5 for a more detailed discussion of random variation and formulas for calculating standard errors for death rates and infant mortality rates).

Table Estimated population by age group, Hispanic origin and race, by sex: United States, 2024

[Populations are postcensal estimates based on the blended base produced by the U.S. Census Bureau in place of the April 1, 2020, decennial population count. The blended base consists of Vintage 2020 Population Estimates for April 1, 2020 (based on April 1, 2010, decennial census), blended with the 2024 Demographic Analysis estimates and the 2024 Census Edited File (see https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2024/methods-statement-v2024.pdf); see Technical Notes in this report]

Hispanic origin and race and sex | Age group (years)
Hispanic origin and race and sex | Total | Under 1 year | 1–4 | 5–9 | 10–14 | 15–19 | 20–24 | 25–34 | 35–44 | 45–54 | 55–64 | 65 and older | 65–74 | 75–84 | 85 and older
Total^*^ | 340,110,988 | 3,615,598 | 14,983,716 | 20,197,672 | 20,901,154 | 22,375,825 | 22,421,936 | 46,453,864 | 45,539,224 | 40,780,356 | 41,661,725 | 61,179,918 | 35,444,962 | 19,299,813 | 6,435,143
Male | 168,337,882 | 1,846,708 | 7,654,335 | 10,319,642 | 10,701,148 | 11,461,769 | 11,451,815 | 23,518,451 | 22,955,948 | 20,322,445 | 20,415,008 | 27,690,613 | 16,699,669 | 8,576,931 | 2,414,013
Female | 171,773,106 | 1,768,890 | 7,329,381 | 9,878,030 | 10,200,006 | 10,914,056 | 10,970,121 | 22,935,413 | 22,583,276 | 20,457,911 | 21,246,717 | 33,489,305 | 18,745,293 | 10,722,882 | 4,021,130
Hispanic^†^ | 68,086,153 | 1,040,823 | 4,193,818 | 5,366,943 | 5,507,399 | 5,922,748 | 5,562,878 | 10,469,992 | 9,669,826 | 8,204,827 | 6,174,395 | 5,972,504 | 3,700,056 | 1,692,377 | 580,071
Male | 34,456,727 | 529,655 | 2,135,470 | 2,732,422 | 2,809,910 | 3,041,286 | 2,853,448 | 5,369,668 | 5,054,434 | 4,174,795 | 3,081,098 | 2,674,541 | 1,735,291 | 724,503 | 214,747
Female | 33,629,426 | 511,168 | 2,058,348 | 2,634,521 | 2,697,489 | 2,881,462 | 2,709,430 | 5,100,324 | 4,615,392 | 4,030,032 | 3,093,297 | 3,297,963 | 1,964,765 | 967,874 | 365,324
Non-Hispanic, single race^§^:
American Indian and Alaska Native | 2,442,428 | 23,470 | 99,249 | 149,758 | 166,062 | 180,327 | 176,618 | 369,853 | 327,675 | 277,301 | 287,924 | 384,191 | 231,471 | 114,311 | 38,409
Male | 1,203,790 | 11,990 | 50,656 | 76,327 | 84,757 | 91,474 | 89,645 | 186,862 | 163,704 | 136,582 | 138,013 | 173,780 | 106,573 | 51,820 | 15,387
Female | 1,238,638 | 11,480 | 48,593 | 73,431 | 81,305 | 88,853 | 86,973 | 182,991 | 163,971 | 140,719 | 149,911 | 210,411 | 124,898 | 62,491 | 23,022
Asian | 22,080,844 | 197,752 | 889,718 | 1,241,904 | 1,215,577 | 1,243,491 | 1,448,194 | 3,509,664 | 3,676,704 | 3,038,184 | 2,426,480 | 3,193,176 | 1,860,303 | 966,899 | 365,974
Male | 10,609,401 | 101,858 | 457,097 | 638,179 | 624,026 | 633,289 | 731,215 | 1,711,302 | 1,769,729 | 1,428,552 | 1,124,974 | 1,389,180 | 825,541 | 419,463 | 144,176
Female | 11,471,443 | 95,894 | 432,621 | 603,725 | 591,551 | 610,202 | 716,979 | 1,798,362 | 1,906,975 | 1,609,632 | 1,301,506 | 1,803,996 | 1,034,762 | 547,436 | 221,798
Black | 42,951,595 | 505,268 | 2,116,198 | 2,787,893 | 2,871,519 | 3,060,683 | 3,021,064 | 6,622,739 | 5,945,447 | 5,109,699 | 4,976,071 | 5,935,014 | 3,740,744 | 1,668,411 | 525,859
Male | 20,604,933 | 256,713 | 1,072,902 | 1,408,942 | 1,459,267 | 1,552,657 | 1,518,385 | 3,300,252 | 2,877,833 | 2,406,434 | 2,301,909 | 2,449,639 | 1,626,967 | 654,917 | 167,755
Female | 22,346,662 | 248,555 | 1043296.0 | 1,378,951 | 1,412,252 | 1,508,026 | 1,502,679 | 3,322,487 | 3,067,614 | 2,703,265 | 2,674,162 | 3,485,375 | 2,113,777 | 1,013,494 | 358,104
Native Hawaiian or Other Pacific Islander | 674,821 | 8,380 | 35,037 | 47,746 | 45,518 | 47,426 | 47,963 | 101,355 | 106,709 | 81,403 | 71,212 | 82,072 | 50,346 | 23,976 | 7,750
Male | 340,511 | 4,360 | 18,187 | 24,546 | 23,339 | 24,037 | 24,445 | 51,663 | 54,887 | 41,458 | 35,057 | 38,532 | 24,187 | 11,133 | 3,212
Female | 334,310 | 4,020 | 16,850 | 23,200 | 22,179 | 23,389 | 23,518 | 49,692 | 51,822 | 39,945 | 36,155 | 43,540 | 26,159 | 12,843 | 4,538
White | 195,433,224 | 1,645,734 | 6,856,514 | 9,593,984 | 10,108,341 | 10,995,853 | 11,383,326 | 24,101,449 | 24,970,823 | 23,478,524 | 27,258,546 | 45,040,130 | 25,517,336 | 14,665,604 | 4,857,190
Male | 96,929,366 | 843,077 | 3,515,598 | 4,922,961 | 5,194,825 | 5,647,586 | 5,838,655 | 12,259,659 | 12,633,271 | 11,856,486 | 13,513,864 | 20,703,384 | 12,219,288 | 6,639,366 | 1,844,730
Female | 98,503,858 | 802,657 | 3,340,916 | 4,671,023 | 4,913,516 | 5,348,267 | 5,544,671 | 11,841,790 | 12,337,552 | 11,622,038 | 13,744,682 | 24,336,746 | 13,298,048 | 8,026,238 | 3,012,460

* Includes origin not stated, origin not classifiable, and two or more races reported; see Technical Notes.

†Includes people of Hispanic origin of any race.

§Only one race was reported.

SOURCE: National Center for Health Statistics, estimates as of July 1, 2024, U.S. resident population by age, sex, race, and Hispanic origin prepared by U.S. Census Bureau, 2026.

## References

1 National Office of Vital Statistics. Leading causes of death: United States and each state, 1949. Vital statistics—Special reports, national summaries. 1952;36(20).
2 National Office of Vital Statistics. Summary report of the third annual meeting of the Public Health Conference on Records and Statistics. 1951.
3 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist. 1997;62(210):58782–90. Available from: https://www.govinfo.gov/content/pkg/FR-1997-10-30/pdf/97-28653.pdf.
4 Heron M. Comparability of race-specific mortality data based on 1977 versus 1997 reporting standards. Natl Vital Stat Rep. 2021 Apr;70(3):1–31. DOI: 10.15620/cdc:103476.
5 Xu JQ, Murphy SL, Kochanek KD, Arias E. Deaths: Final data for 2024. Natl Vital Stat Rep. 2027. [Forthcoming].
6 World Health Organization. International statistical classification of diseases and related health problems, 10th revision (ICD–10). 2008 ed. 2009.
7 Anderson RN, Rosenberg HM. Age standardization of death rates: Implementation of the year 2000 standard. Natl Vital Stat Rep. 1998 Oct;47(3):1–17. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr47/nvs47_03.pdf.
8 National Center for Health Statistics. Instruction manual, part 9: ICD–10 cause-of-death lists for tabulating mortality statistics. 2020. Available from: https://www.cdc.gov/nchs/data/dvs/Part9InstructionManual2020-508.pdf.
9 Heron M, Hoyert DL, Murphy SL, Xu JQ, Kochanek KD, Tejada-Vera B. Deaths: Final data for 2006. Natl Vital Stat Rep. 2009 Apr;57(14):1–134. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr57/nvsr57_14.pdf.
10 Heron M. Deaths: Leading causes for 2006. Natl Vital Stat Rep. 2010 Mar;58(14):1–100. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr58/nvsr58_14.pdf.
11 Murphy SL. Deaths: Final data for 1998. Natl Vital Stat Rep. 2000 Jul;48(11):1–105. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr48/nvs48_11.pdf.
12 Gardner P, Rosenberg HM, Wilson RW. Leading causes of death by age, sex, race, and Hispanic origin: United States, 1992. Vital Health Stat. 1996 Jun;20(29):1–94. Available from: https://www.cdc.gov/nchs/data/series/sr_20/sr20_029.pdf.
13 National Center for Health Statistics. U.S. Standard Certificate of Death, 2003 revision. 2003. Available from: https://www.cdc.gov/nchs/data/dvs/DEATH11-03final-acc.pdf.
14 Ingram DD, Parker JD, Schenker N, Weed JA, Hamilton B, Arias E, Madans JH. United States Census 2000 population with bridged race categories. Vital Health Stat 2. 2003 Sep;(135):1–62. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_135.pdf.
15 Office of Management and Budget. Race and ethnic standards for federal statistics and administrative reporting. Statistical Policy Directive no 15. 1977. Available from https://wonder.cdc.gov/wonder/help/populations/bridged-race/directive15.html.
16 Arias E, Heron M, Hakes JK. The validity of race and Hispanic-origin reporting on death certificates in the United States: An update. Vital Health Stat 2. 2016 Aug;(172):1–21. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_172.pdf.
17 Arias E, Xu JQ, Curtin S, Bastian B, Tejada-Vera B. Mortality profile of the non-Hispanic American Indian or Alaska Native population, 2019. National Vital Stat Rep. 2021 Nov;70(12):1–27. DOI: 10.15620/cdc:110370.
18 Tejada-Vera B, Bastian BA, Curtin SC. Deaths: Leading causes for 2023. National Vital Stat Rep. 2025 Sep;74(10):1–115. DOI: 10.15620/cdc:174607.
19 Sorlie PD, Rogot E, Johnson NJ. Validity of demographic characteristics on the death certificate. Epidemiology. 1992 Mar;3(2):181–4.1576225
20 Rosenberg HM, Maurer JD, Sorlie PD, Johnson NJ, MacDorman MF, Hoyert DL, et al. Quality of death rates by race and Hispanic origin: A summary of current research, 1999. Vital Health Stat 2. 1999 Sep;(128):1–13. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_128.pdf.
21 Arias E, Schauman WS, Eschbach K, Sorlie PD, Backlund E. The validity of race and Hispanic origin reporting on death certificates in the United States. Vital Health Stat 2. 2008 Oct;(148):1–23. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_148.pdf.
22 Arias E, Eschbach K, Schauman WS, Backlund EL, Sorlie PD. The Hispanic mortality advantage and ethnic misclassification on U.S. death certificates. Am J Public Health. 2010 Apr;100(Suppl 1):S171–7.19762677
23 Ely DM, Driscoll AK. Infant mortality in the United States, 2024: Data from the period linked birth/infant death file. Natl Vital Stat Rep. 2026 Jun;75(3):1–21. DOI: 10.15620/cdc:252441.
24 National Center for Health Statistics. Instruction manual, part 2a: Instructions for classifying the underlying cause of death, 2017. Available from: https://www.cdc.gov/nchs/data/dvs/2a_2017.pdf.
25 National Center for Health Statistics. Instruction manual, part 2b: Instructions for classifying multiple causes of death, 2017. Available from: https://www.cdc.gov/nchs/data/dvs/2b_2017.pdf.
26 National Center for Health Statistics. Instruction manual, part 2e, volume 1: ICD–10, mortality. Tabular list, 2017. Available from: https://www.cdc.gov/nchs/data/dvs/2e_volume1_2017.pdf.
27 National Center for Health Statistics. Instruction manual, part 11: Computer edits for mortality data, including separate section for fetal deaths, effective 2023. Available from: https://www.cdc.gov/nchs/data/dvs/2023_PT11_A.pdf.
28 National Center for Health Statistics. Instruction manual, part 2c: Vital statistics ICD–10 ACME decision tables for classifying underlying causes of death, 2016. Available from: https://www.cdc.gov/nchs/data/dvs/2c_2016.pdf.
29 National Center for Health Statistics. Instruction manual, part 2g: Data entry instructions for the Mortality Medical Indexing, Classification, and Retrieval System (MICAR), 1996–1997. 1996. Available from: https://www.cdc.gov/nchs/data/dvs/2gmanual.pdf.
30 National Center for Health Statistics. Instruction manual, part 2h: Dictionary of valid terms for the Mortality Medical Indexing, Classification, and Retrieval System (MICAR), 1991.
31 National Center for Health Statistics. Instruction manual, part 2s: SuperMICAR data entry instructions, 2011. Available from: https://www.cdc.gov/nchs/data/dvs/2011_2s.pdf.
32 Chamblee RF, Evans MC. TRANSAX: The NCHS system for producing multiple cause-of-death statistics, 1968–78. National Center for Health Statistics. Vital Health Stat 1. 1986 Jun;(20):1–83. Available from: https://www.cdc.gov/nchs/data/series/sr_01/sr01_020acc.pdf.
33 Israel RA, Rosenberg HM, Curtin LR. Analytical potential for multiple cause-of-death data. Am J Epidemiol. 1986 Aug;124(2):161–79.3524199
34 National Center for Health Statistics. Mortality multiple cause-of-death public use record, 2024 documentation. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/mortality/2024-Mortality-Public-Use-File-Documentation.pdf.
35 National Center for Health Statistics. User guide to the 2021 natality public use file. Available from: https://www.cdc.gov/nchs/data_access/Vitalstatsonline.htm.
36 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D, et al. National Center for Health Statistics data presentation standards for rates and counts. Vital Health Stat 2. 2023 Mar;(200):1−26. DOI: 10.15620/cdc:124368.
37 National Center for Health Statistics. Implementation of new data presentation standards for rates and counts for mortality. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/mortality/presentation-standards-mortality-2024.pdf.
38 U.S. Census Bureau. Vintage 2024 annual state resident population estimates for 6 race groups (5 race alone groups and two or more races) by age, sex, and Hispanic origin: April 1, 2020, to July 1, 2024. 2024. Available from https://www2.census.gov/programs-surveys/popest/datasets/2020-2024/state/asrh (SC-EST2024-ALLDATA6).
39 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2024. Natl Vital Stat Rep. 2026 Jun;75(2):1–48. DOI: 10.15620/cdc:252440.

National Center for Health Statistics

Carolyn M. Greene, M.D., Acting Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science