# Volume 75, Number 4 Trends and Characteristics in Gestational Hypertension: United States, 2016–2024

### Objective

This report presents data on trends in gestational hypertension (hypertension diagnosed during pregnancy) among mothers giving birth in the United States from 2016 through 2024, as well as rates by selected maternal and infant characteristics for 2016 and 2024.

### Methods

Data are from birth certificates and are based on 100% of births registered in the United States for 2016 through 2024. Descriptive tabulations on trends in gestational hypertension rates from 2016 through 2024 and rates by maternal race and Hispanic origin, age, body mass index, state of residence, and plurality for 2016 and 2024 are presented.

### Results

Among mothers giving birth in 2024, the overall rate of gestational hypertension was 10.4%, an increase of 73% from 2016 (6.0%). In 2024, the rate of gestational hypertension varied by maternal race and Hispanic origin, ranging from a low of 7.1% for Asian non-Hispanic mothers to a high of 13.2% for American Indian and Alaska Native non-Hispanic mothers. By age, the rate was lowest for mothers younger than age 20 and 30–34 and highest for mothers 40 and older. The rate of gestational hypertension rose with increasing prepregnancy body mass index. By plurality, the rate of gestational hypertension was nearly 2 times higher for mothers with a twin or higher-order multiple birth than mothers with a singleton birth. By state, the rate of gestational hypertension was lower than 9.0% in nine states (New Jersey, California, Massachusetts, Utah, Nevada, New York, Idaho, Tennessee, and New Mexico) and the District of Columbia and was 13.0% or more in eight states (Minnesota, Oregon, Wyoming, New Hampshire, Ohio, Alabama, Alaska, and Louisiana).

## Introduction

Hypertensive disorders in pregnancy, which include chronic hypertension, chronic hypertension with superimposed preeclampsia, gestational hypertension, preeclampsia, and eclampsia (1–5), are common pregnancy complications and are among the leading causes of maternal morbidity and mortality in the United States (4,6,7). These disorders affect about 5%–16% of pregnancies and have been increasing over time (4,5,8–10). One study among delivery hospitalizations found that increases in pregnancy-associated hypertension (all hypertensive disorders during pregnancy except chronic hypertension) were largely responsible for the overall increase in hypertensive disorders in pregnancy, at least in more recent years (5). Adverse health outcomes of hypertensive disorders in pregnancy for the mother include placental abruption, organ damage or failure, maternal mortality, and cardiovascular disease later in life (1,4,6,7,9,11). Adverse perinatal outcomes include stillbirth, neonatal mortality, intrauterine growth restriction, preterm birth, and low birthweight (1,4,9,12).

On the birth certificate, maternal hypertension (elevation of blood pressure above normal for age, sex, and physiological condition) is divided into two mutually exclusive categories: prepregnancy hypertension (hypertension diagnosed prior to the onset of this pregnancy, which includes chronic hypertension) and gestational hypertension (hypertension diagnosed during this pregnancy, which includes pregnancy-induced hypertension and preeclampsia). A third category, eclampsia (hypertension with proteinuria with generalized seizures or coma), may be selected alone or in combination with prepregnancy or gestational hypertension (13,14). Due to changes in the diagnostic criteria for chronic hypertension in nonpregnant patients in 2017 and subnational birth data for eclampsia until 2022, only gestational hypertension is the focus of this report (15,16).

Birth certificate data on gestational hypertension, available since 1989, show that from 1989 to 2016, the rate of gestational hypertension increased 108% (17,18). This report describes overall trends in gestational hypertension from 2016, the first year for which national data are available based on the 2003 revision of the U.S. Standard Certificate of Live Birth (19) (which includes race data consistent with the 1997 Office of Management and Budget standards and data to calculate body mass index), through 2024, as well as rates of gestational hypertension by maternal race and Hispanic origin, age, body mass index, state of residence, and plurality for 2016 and 2024.

## Methods

This analysis uses data from the birth certificate and is based on 100% of births registered in the United States for 2016 through 2024. Trend analysis on the overall rate of gestational hypertension was performed using data from 2016 through 2024 and a more detailed analysis was conducted on 2016 and 2024 data for rates of gestational hypertension by maternal race and Hispanic origin, age, body mass index, state of residence, and plurality.

The gestational hypertension item was added to the birth certificate with the 1989 revision. Birth certificate data on gestational hypertension is recommended to be collected from the mother’s medical records, with the prenatal care record as the preferred source (14). Mothers are to be reported as having gestational hypertension if there is a diagnosis of elevated blood pressure above normal for age, sex, and physiological condition diagnosed in this pregnancy (includes both pregnancy-induced hypertension and preeclampsia) in her medical record (20). This definition differs from the clinical definition, which defines gestational hypertension as high blood pressure that develops after 20 weeks of pregnancy and ends shortly after delivery (21–23). Of the 3,628,934 births registered in the United States for 2024, 7,301, or 0.2%, were missing information on gestational hypertension. Data were also missing for 2.4% (88,355) of births for body mass index (BMI) and 1.0% (35,452) for maternal Hispanic origin. Births with missing values for race (304,965 or 8.4%), age (486, 0.01%), and plurality (1,598, 0.04%) were imputed. Records with missing information were excluded from analyses.

Race and Hispanic origin are reported separately on the birth certificate and are self-reported by the mother. All race and Hispanic-origin data are based on single-race reporting and are consistent with the 1997 Office of Management and Budget standards (24). The maternal race and Hispanic origin categories presented are: American Indian and Alaska Native non-Hispanic, Asian non-Hispanic, Black non-Hispanic, Native Hawaiian or Other Pacific Islander non-Hispanic, White non-Hispanic, and Hispanic. In this report, text references to non-Hispanic single-race groups omit the term “non-Hispanic.”

Maternal prepregnancy BMI is calculated from prepregnancy weight and height according to the following formula (25):

(m o t h e r ' s p r e p r e g n a n c y w e i g h t ( l b ))/(m o t h e r ' s h e i g h t ( i n )^2^) • 703

The National Center for Health Statistics (NCHS) provides a calculated categorization of maternal prepregnancy BMI that aligns with that established by the National Heart, Lung, and Blood Institute (26) for all adults. Categories are:

- Underweight = BMI less than 18.5
- Normal weight = BMI of 18.5 to less than 25.0
- Overweight = BMI of 25.0 to less than 30.0
- Obese = BMI of 30.0 and over

Rates of gestational hypertension are expressed as the number of live births to women with gestational hypertension per 100 live births. All statements about differences in rates in the text have been tested for statistical significance, and a statement that a given rate is higher or lower than another rate indicates that the rates are significantly different using a two-tailed z test at the alpha level of 0.05 (27). References to trends in rates over time (such as, trends in rates for 2016 through 2024) are statistically significant at the 0.05 level and were evaluated using the Joinpoint Regression Program (28). All estimates met NCHS standards for presentation (29,30).

## Results

### Overall trends

- The number of cases of gestational hypertension increased 60% from 2016 (235,693) to 2024 (377,267), an average annual increase of 6% (Table 1).
- The rate of gestational hypertension increased 73% from 2016 (6.0%) to 2024 (10.4%), an average annual increase of 7% (Table 1 and Figure 1).

Table 1

Number of cases and rate of gestational hypertension: United States, 2016–2024

[Rates are number of births to women with gestational hypertension per 100 births]
Year | Total births | Number of cases of gestational hypertension | Rate (95% confidence interval) | | Not stated^*^
2024 | 3,628,934 | 377,267 | 10.4 | (10.4–10.4) | 7,301
2023 | 3,596,017 | 361,780 | 10.1 | (10.0–10.1) | 5,752
2022 | 3,667,758 | 348,420 | 9.5 | (9.5–9.5) | 6,605
2021 | 3,664,292 | 333,633 | 9.1 | (9.1–9.1) | 5,205
2020 | 3,613,647 | 304,293 | 8.4 | (8.4–8.5) | 4,063
2019 | 3,747,540 | 291,626 | 7.8 | (7.8–7.8) | 3,284
2018 | 3,791,712 | 271,596 | 7.2 | (7.1–7.2) | 2,882
2017 | 3,855,500 | 248,282 | 6.4 | (6.4–6.5) | 3,711
2016 | 3,945,875 | 235,693 | 6.0 | (6.0–6.0) | 3,781

* No response reported for the “risk factors in this pregnancy” item on the birth certificate.

NOTE: Significant increasing trend from 2016 to 2024 (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 1 Rate of gestational hypertension: United States, 2016–2024

NOTE: Significant increasing trend from 2016 to 2024 (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 1 is a line chart showing the rate of gestational hypertension by year for the time period 2016 through 2024.

### Trends and differences by maternal race and Hispanic origin

- From 2016 to 2024, the rate of gestational hypertension increased for each of the six largest race and Hispanic-origin groups: 66% for Black (from 7.4% to 12.3%), 73% for Hispanic (4.9% to 8.5%), 74% for American Indian and Alaska Native (7.6% to 13.2%), 77% for Native Hawaiian or Other Pacific Islander (6.0% to 10.6%), 77% for White (6.4% to 11.3%), and 103% for Asian (3.5% to 7.1%) mothers (Table 2 and Figure 2).
- In 2024, the rate of gestational hypertension was lowest for Asian mothers, followed by Hispanic, Native Hawaiian or Other Pacific Islander, White, Black, and American Indian and Alaska Native mothers. This pattern was generally similar for 2016 (Table 2 and Figure 2).

Table 2

Number of cases and rate of gestational hypertension, by selected characteristics: United States, 2016 and 2024[Rates are number of births to women with gestational hypertension per 100 births in specified group]

Characteristic | Rate (95% confidence interval) | | | | Percent change
Characteristic | 2016 | | 2024 | | 2016–2024
Total | 6.0 | (6.0–6.0) | 10.4 | (10.4–10.4) | 73^*^
Race and Hispanic origin
Non-Hispanic, single race^†^
American Indian and Alaska Native^§,¶^ | 7.6 | (7.3–7.9) | 13.2 | (12.8–13.6) | 74^*^
Asian^¶,**^ | 3.5 | (3.4–3.5) | 7.1 | (7.0–7.2) | 103^*^
Black^¶,††^ | 7.4 | (7.3–7.4) | 12.3 | (12.2–12.4) | 66^*^
Native Hawaiian or Other Pacific Islander^¶,§§^ | 6.0 | (5.5–6.5) | 10.6 | (10.0–11.2) | 77^*^
White^¶,¶¶^ | 6.4 | (6.4–6.4) | 11.3 | (11.3–11.4) | 77^*^
Hispanic^¶,**,,^*** | 4.9 | (4.8–4.9) | 8.5 | (8.5–8.6) | 73^*^
Age (years)
Younger than 20^†††^ | 6.4 | (6.3–6.5) | 10.2 | (10.0–10.3) | 59^*^
20–24 | 5.9 | (5.8–5.9) | 10.5 | (10.4–10.6) | 78^*^
25–29^§§§^ | 5.7 | (5.7–5.8) | 10.5 | (10.4–10.5) | 84^*^
30–34^†††^ | 5.8 | (5.7–5.8) | 10.1 | (10.0–10.1) | 74^*^
35–39 | 6.4 | (6.4–6.5) | 10.5 | (10.4–10.5) | 64^*^
40 or older^¶¶¶^ | 8.2 | (8.1–8.4) | 12.2 | (12.0–12.4) | 49^*^
Body mass index (BMI)
Underweight (BMI less than 18.5)^****^ | 2.7 | (2.6–2.8) | 5.5 | (5.3–5.6) | 104^*^
Normal weight (BMI 18.5–24.9)^****^ | 3.8 | (3.7–3.8) | 6.8 | (6.8–6.9) | 79^*^
Overweight (BMI 25.0–29.9)^****^ | 6.0 | (6.0–6.1) | 10.0 | (9.9–10.0) | 67^*^
Obese (BMI greater than 29.9)^****^ | 10.2 | (10.1–10.2) | 15.4 | (15.4–15.5) | 51^*^
Plurality
Singleton^††††^ | 5.8 | (5.7–5.8) | 10.2 | (10.2–10.2) | 76^*^
Twin and higher order^††††,§§§§^ | 12.4 | (12.2–12.5) | 17.0 | (16.8–17.3) | 37^*^
Characteristic | Number of cases of gestational hypertension | | Number of births | | Not stated^¶¶¶¶^
Characteristic | 2016 | 2024 | 2016 | 2024 | 2016 | 2024
Total | 235,693 | 377,267 | 3,945,875 | 3,628,934 | 3,781 | 7,301
Race and Hispanic origin
Non-Hispanic, single race^†^
American Indian and Alaska Native | 2,372 | 3,163 | 31,452 | 24,021 | 77 | 76
Asian | 8,844 | 16,035 | 254,471 | 226,860 | 145 | 271
Black | 41,191 | 58,075 | 558,622 | 473,377 | 578 | 1,133
Native Hawaiian or Other Pacific Islander | 559 | 1,094 | 9,342 | 10,375 | 5 | 22
White | 131,261 | 201,533 | 2,056,332 | 1,783,156 | 1,895 | 3,143
Hispanic^***^ | 44,675 | 83,941 | 918,447 | 984,092 | 625 | 1,643
Age (years)
Younger than 20 | 13,536 | 14,119 | 212,062 | 139,000 | 235 | 413
20–24 | 47,007 | 63,949 | 803,978 | 611,800 | 825 | 1408
25–29 | 65,727 | 103,494 | 1,149,122 | 990,817 | 1,065 | 1,919
30–34 | 64,213 | 112,079 | 1,111,042 | 1,112,409 | 1,032 | 2,049
35–39 | 35,194 | 65,062 | 547,488 | 622,517 | 493 | 1,174
40 or older | 10,016 | 18,564 | 122,183 | 152,391 | 131 | 338
Body mass index (BMI)
Underweight (BMI less than 18.5) | 3,614 | 5,067 | 134,512 | 92,454 | 120 | 163
Normal weight (BMI 18.5–24.9) | 63,890 | 89,794 | 1,701,087 | 1,319,471 | 1,336 | 1,824
Overweight (BMI 25.0–29.9) | 59,988 | 98,766 | 998,761 | 990,685 | 784 | 1,032
Obese (BMI greater than 29.9) | 102,050 | 175,594 | 1,002,622 | 1,137,969 | 736 | 1,095
Plurality
Singleton | 218,932 | 358,251 | 3,810,149 | 3,517,151 | 3,675 | 7,106
Twin and higher order | 16,761 | 19,016 | 135,726 | 111,783 | 106 | 195

* Significant change (p < 0.05).

† Race and Hispanic origin are reported separately on birth certificates; people of Hispanic origin may be of any race. In this table, non-Hispanic women are classified by race. Race categories are consistent with the 1997 Office of Management and Budget standards. Single race is defined as only one race reported on the birth certificate.

§ Significantly different from all groups except Black non-Hispanic people in 2016 (p < 0.05).

¶ Significantly different from other race and Hispanico-origin groups in 2024 (p < 0.05).

** Significantly different from other race and Hispanic-origin groups in 2016 (p < 0.05).

†† Significantly different from all groups except American Indian and Alaska Native non-Hispanic people in 2016 (p < 0.05).

§§ Significantly different from all groups except White non-Hispanic people in 2016 (p < 0.05).

¶¶ Significantly different from all groups except Native Hawaiian or Other Pacific Islander non-Hispanic people in 2016 (p < 0.05).

*** Includes all people of Hispanic origin of any race.

††† Age group had lowest rate in 2024 (p < 0.05).

§§§ Age group had lowest rate in 2016 (p < 0.05).

¶¶¶ Age group had highest rate in 2016 and 2024 (p < 0.05).

**** Significantly different from other BMI categories in 2016 and 2024 (p < 0.05).

†††† Significantly different from other pluralities in 2016 and 2024 (p < 0.05).

§§§§ Twin, triplet, quadruplet, quintuplet, and higher-order multiple deliveries.

¶¶¶¶ No response reported for the "risk factors in this pregnancy" item on the birth certificate.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 2 Rate of gestational hypertension, by race and Hispanic origin of mother: United States, 2016 and 2024

* Significantly different from other race and Hispanic-origin groups in 2016 (p < 0.05) .

† Significantly different from other race and Hispanic-origin groups in 2024 (p < 0.05).

§ Significantly different from 2016 (p < 0.05).

¶ Significantly different from all groups except White non-Hispanic in 2016 (p < 0.05).

** Significantly different from all groups except Native Hawaiian or Other Pacific Islander non-Hispanic in 2016 (p < 0.05).

†† Significantly different from all groups except American Indian and Alaska Native non-Hispanic in 2016 (p < 0.05).

§§ Significantly different from all groups except Black non-Hispanic in 2016 (p < 0.05).

NOTE: Mothers of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 2 is a bar chart showing the rate of gestational hypertension by race and Hispanic origin of mother for 2016 and 2024.

### Trends and differences by maternal age

- From 2016 to 2024, the rate of gestational hypertension increased for each maternal age group. The rate increased 59% (from 6.4% to 10.2%) for mothers younger than age 20, 78% (5.9% to 10.5%) for mothers ages 20–24, 84% (5.7% to 10.5%) for mothers ages 25–29, 74% (5.8% to 10.1%) for mothers ages 30–34, 64% (6.4% to 10.5%) for mothers ages 35–39, and 49% (8.2% to 12.2%) for mothers ages 40 and older (Table 2 and Figure 3).
- Patterns across age groups differed somewhat between the two years. In 2024, the rate was lowest for mothers younger than age 20 and 30–34 and highest for mothers 40 and older. In 2016, the rate was lowest for mothers ages 25–29 and highest for mothers 40 and older (Table 2 and Figure 3).

Figure 3 Rate of gestational hypertension, by age of mother: United States, 2016 and 2024

* Significantly different from 2016 (p < 0.05).

† Age group with the lowest rate in 2024 (p < 0.05).

§ Age group had lowest rate in 2016 (p < 0.05).

¶ Age group had highest rate in 2016 and 2024 (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 3 is a bar chart showing the rate of gestational hypertension by age of mother for 2016 and 2024.

### Trends and differences by maternal BMI

- From 2016 to 2024, the rate of gestational hypertension increased 104% (from 2.7% to 5.5%) for mothers who were underweight, 79% for those who were normal weight (3.8% to 6.8%), 67% for those who were overweight (6.0% to 10.0%), and 51% for those with obesity (10.2% to 15.4%) (Table 2 and Figure 4).
- In 2024, the rate of gestational hypertension increased with increasing maternal BMI; mothers who were underweight had the lowest rate and those with obesity had the highest rate. This pattern was also observed in 2016 (Table 2 and Figure 4).

Figure 4 Rate of gestational hypertension, by body mass index: United States, 2016 and 2024

* Significantly different from other body mass index (BMI) categories in 2016 and 2024 (p < 0.05).

† Significantly different from 2016 (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 4 is a bar chart showing the rate of gestational hypertension by maternal prepregnancy body mass index for 2016 and 2024.

### Trends and differences by plurality

- From 2016 to 2024, the rate of gestational hypertension increased 76% (from 5.8% to 10.2%) for mothers with a singleton birth and 37% for mothers with a twin or higher-order multiple birth (12.4% to 17.0%) (Table 2 and Figure 5).
- In 2024, the rate of gestational hypertension was nearly twice as high for mothers with a twin or higher-order multiple birth compared with that for mothers with a singleton birth. This pattern was generally similar in 2016 (Table 2 and Figure 5).

Figure 5 Rate of gestational hypertension, by plurality: United States, 2016 and 2024

* Significantly different from other pluralities in 2016 and 2024 (p < 0.05).

† Significantly different from 2016 (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 5 is a bar chart showing the rate of gestational hypertension by plurality for 2016 and 2024.

### Trends and differences by state of residence

- From 2016 to 2024, the rate of gestational hypertension increased in all 50 states and the District of Columbia, with increases ranging from 21% in Idaho to 144% in Hawaii (Table 3 and Figure 6).
- In 2024, the rate of gestational hypertension was less than 9.0% in nine states—New Jersey (6.9%), California (8.3%), Massachusetts (8.3%), Utah (8.3%), Nevada (8.4%), New York (8.5%), Idaho (8.7%), Tennessee (8.7%), and New Mexico (8.8%)—and in the District of Columbia (8.3%), and was 13.0% or higher in eight states—Minnesota (13.0%), Oregon (13.1%), Wyoming (13.1%), New Hampshire (13.3%), Ohio (13.6%), Alabama (13.7%), Alaska (14.5%), and Louisiana (14.6%) (Table 3 and Figure 6).

Table 3

Number of cases and rate of gestational hypertension, by state of residence of mother: United States, 2016 and 2024

[Rates are number of births to women with gestational hypertension per 100 births in specified group]
Reporting area | Rate (95% confidence interval) | | | | Percent change
Reporting area | 2016 | | 2024 | | 2016–2024
Total | 6.0 | (6.0–6.0) | 10.4 | (10.4–10.4) | 73*
Alabama | 7.2 | (7.0–7.5) | 13.7 | (13.4–14.0) | 90*
Alaska | 8.9 | (8.4–9.5) | 14.5 | (13.8–15.2) | 63*
Arizona | 6.2 | (6.1–6.4) | 10.9 | (10.7–11.1) | 76*
Arkansas | 5.2 | (5.0–5.5) | 10.8 | (10.5–11.2) | 108*
California | 3.9 | (3.9–4.0) | 8.3 | (8.2–8.4) | 113*
Colorado | 5.9 | (5.8–6.1) | 12.9 | (12.7–13.2) | 119*
Connecticut | 5.8 | (5.6–6.1) | 9.7 | (9.3–10.0) | 67*
Delaware | 7.4 | (6.9–7.9) | 10.8 | (10.2–11.4) | 46*
District of Columbia | 5.9 | (5.4–6.4) | 8.3 | (7.7–8.9) | 41*
Florida | 5.5 | (5.4–5.6) | 10.1 | (10.0–10.2) | 84*
Georgia | 6.0 | (5.9–6.2) | 10.6 | (10.5–10.8) | 77*
Hawaii | 4.3 | (4.0–4.6) | 10.5 | (10.0–11.0) | 144*
Idaho | 7.2 | (6.8–7.5) | 8.7 | (8.4–9.1) | 21*
Illinois | 6.8 | (6.7–7.0) | 12.0 | (11.8–12.2) | 76*
Indiana | 6.8 | (6.6–7.0) | 11.2 | (10.9–11.4) | 65*
Iowa | 6.6 | (6.3–6.8) | 11.7 | (11.4–12.1) | 77*
Kansas | 6.6 | (6.3–6.8) | 11.1 | (10.8–11.4) | 68*
Kentucky | 7.9 | (7.6–8.1) | 11.7 | (11.4–12.0) | 48*
Louisiana | 9.4 | (9.1–9.6) | 14.6 | (14.3–14.9) | 55*
Maine | 7.0 | (6.6–7.5) | 12.2 | (11.6–12.8) | 74*
Maryland | 6.2 | (6.0–6.4) | 11.8 | (11.6–12.1) | 90*
Massachusetts | 4.1 | (3.9–4.2) | 8.3 | (8.1–8.5) | 102*
Michigan | 6.5 | (6.4–6.7) | 10.6 | (10.4–10.8) | 63*
Minnesota | 6.7 | (6.5–6.9) | 13.0 | (12.7–13.2) | 94*
Mississippi | 6.4 | (6.2–6.7) | 11.1 | (10.8–11.4) | 73*
Missouri | 7.4 | (7.2–7.6) | 12.0 | (11.7–12.2) | 62*
Montana | 6.1 | (5.7–6.5) | 11.3 | (10.7–11.8) | 85*
Nebraska | 5.7 | (5.4–6.0) | 10.8 | (10.4–11.1) | 89*
Nevada | 4.5 | (4.3–4.8) | 8.4 | (8.1–8.7) | 87*
New Hampshire | 8.2 | (7.7–8.7) | 13.3 | (12.7–13.9) | 62*
New Jersey | 4.7 | (4.6–4.8) | 6.9 | (6.8–7.1) | 47*
New Mexico | 6.5 | (6.1–6.8) | 8.8 | (8.5–9.2) | 35*
New York | 6.4 | (6.3–6.5) | 8.5 | (8.3–8.6) | 33*
North Carolina | 6.7 | (6.6–6.9) | 10.7 | (10.5–10.9) | 60*
North Dakota | 5.7 | (5.3–6.1) | 11.3 | (10.7–11.9) | 98*
Ohio | 8.1 | (7.9–8.2) | 13.6 | (13.4–13.8) | 68*
Oklahoma | 5.8 | (5.6–6.0) | 9.4 | (9.1–9.7) | 62*
Oregon | 7.3 | (7.1–7.6) | 13.1 | (12.8–13.5) | 79*
Pennsylvania | 5.5 | (5.4–5.6) | 12.9 | (12.7–13.1) | 135*
Rhode Island | 6.6 | (6.1–7.0) | 12.0 | (11.4–12.7) | 82*
South Carolina | 7.4 | (7.2–7.6) | 12.8 | (12.5–13.0) | 73*
South Dakota | 5.9 | (5.5–6.3) | 9.7 | (9.2–10.3) | 64*
Tennessee | 5.6 | (5.5–5.8) | 8.7 | (8.6–8.9) | 55*
Texas | 6.1 | (6.0–6.2) | 9.2 | (9.1–9.3) | 51*
Utah | 5.8 | (5.6–6.0) | 8.3 | (8.0–8.5) | 43*
Vermont | 8.1 | (7.4–8.8) | 12.1 | (11.2–13.0) | 49*
Virginia | 4.5 | (4.3–4.6) | 10.0 | (9.8–10.2) | 122*
Washington | 6.3 | (6.2–6.5) | 11.8 | (11.6–12.0) | 87*
West Virginia | 6.6 | (6.2–6.9) | 12.1 | (11.6–12.6) | 83*
Wisconsin | 6.2 | (6.0–6.4) | 11.4 | (11.1–11.6) | 84*
Wyoming | 5.6 | (5.1–6.1) | 13.1 | (12.3–14.0) | 134*
Total | 235,693 | 377,267 | 3,945,875 | 3,628,934 | 3,781 | 7,301
Alabama | 4,283 | 7,924 | 59,151 | 57,934 | 3 | 5
Alaska | 996 | 1,287 | 11,209 | 8,943 | 75 | 66
Arizona | 5,275 | 8,601 | 84,520 | 78,711 | § | 2
Arkansas | 2,007 | 3,837 | 38,274 | 35,395 | § | 2
California | 19,219 | 33,450 | 488,827 | 402,075 | 3 | 186
Colorado | 3,956 | 8,309 | 66,613 | 64,268 | 12 | 32
Connecticut | 2,062 | 3,338 | 36,015 | 34,599 | 694 | 29
Delaware | 815 | 1,134 | 10,992 | 10,550 | 1 | 54
District of Columbia | 581 | 630 | 9,858 | 7,616 | 15 | 3
Florida | 12,336 | 22,457 | 225,022 | 224,389 | 416 | 2,289
Georgia | 7,810 | 13,427 | 130,042 | 126,437 | 348 | 113
Hawaii | 776 | 1,562 | 18,059 | 14,917 | § | §
Idaho | 1,606 | 2,031 | 22,482 | 23,276 | 24 | 19
Illinois | 10,543 | 15,106 | 154,445 | 125,731 | 226 | 128
Indiana | 5,650 | 8,895 | 83,091 | 80,257 | 4 | 542
Iowa | 2,595 | 4,277 | 39,403 | 36,436 | 1 | 7
Kansas | 2,510 | 3,770 | 38,053 | 33,984 | § | 1
Kentucky | 4,337 | 6,184 | 55,449 | 52,913 | 281 | 93
Louisiana | 5,908 | 7,804 | 63,178 | 53,305 | § | §
Maine | 894 | 1,414 | 12,705 | 11,601 | 15 | 7
Maryland | 4,548 | 7,771 | 73,136 | 65,797 | 11 | 6
Massachusetts | 2,915 | 5,659 | 71,317 | 68,184 | 96 | 184
Michigan | 7,370 | 10,509 | 113,315 | 99,525 | 268 | 312
Minnesota | 4,649 | 8,049 | 69,749 | 62,110 | 64 | 65
Mississippi | 2,435 | 3,711 | 37,928 | 33,473 | 11 | 4
Missouri | 5,502 | 8,127 | 74,705 | 67,998 | 1 | 2
Montana | 751 | 1,276 | 12,282 | 11,331 | 12 | §
Nebraska | 1,510 | 2,665 | 26,589 | 24,785 | 37 | 20
Nevada | 1,646 | 2,722 | 36,260 | 32,381 | § | 1
New Hampshire | 995 | 1,559 | 12,267 | 11,770 | 107 | 34
New Jersey | 4,807 | 7,028 | 102,647 | 101,372 | 7 | 12
New Mexico | 1,594 | 1,887 | 24,692 | 21,328 | § | 4
New York | 14,897 | 17,332 | 234,283 | 205,489 | 218 | 462
North Carolina | 8,107 | 13,086 | 120,779 | 122,856 | 16 | 457
North Dakota | 649 | 1,090 | 11,383 | 9,634 | § | 1
Ohio | 11,147 | 17,212 | 138,085 | 126,795 | 27 | 17
Oklahoma | 3,029 | 4,503 | 52,592 | 47,962 | 1 | 6
Oregon | 3,341 | 5,110 | 45,535 | 38,963 | 2 | 1
Pennsylvania | 7,689 | 16,342 | 139,409 | 127,299 | 21 | 535
Rhode Island | 707 | 1,203 | 10,798 | 10,009 | 7 | 11
South Carolina | 4,248 | 7,500 | 57,342 | 58,768 | 2 | 68
South Dakota | 724 | 1,110 | 12,275 | 11,451 | 1 | 28
Tennessee | 4,557 | 7,334 | 80,807 | 83,833 | 4 | 3
Texas | 24,273 | 35,854 | 398,047 | 390,828 | 2 | 824
Utah | 2,942 | 3,858 | 50,464 | 46,664 | § | 1
Vermont | 466 | 608 | 5,756 | 5,023 | § | §
Virginia | 4,571 | 9,372 | 102,460 | 94,054 | 4 | 13
Washington | 5,702 | 9,744 | 90,505 | 83,118 | 433 | 344
West Virginia | 1,245 | 2,066 | 19,079 | 17,022 | 98 | 1
Wisconsin | 4,103 | 6,743 | 66,615 | 59,686 | 213 | 305
Wyoming | 415 | 800 | 7,386 | 6,089 | § | 2

* Significant change (p < 0.05).

† No response reported for the "risk factors in this pregnancy" item on the birth certificate.

§ Quantity 0.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 6 Rate of gestational hypertension, by state for 2024, and percent change in rate from 2016 to 2024: Each state and the District of Columbia

NOTE: Rate per 100 live births.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 6 is a map of the United States showing the rate of gestational hypertension by state for 2024, and percent change in rate from 2016 to 2024 for each state and the District of Columbia.

## Discussion

In 2024, 1 out of every 10 mothers (10.4%) giving birth in the United States was diagnosed with gestational hypertension. The rate has increased steadily since 2016 (6.0%), for an overall increase of 73% and an average annual increase of 7%. From 2016 to 2024, gestational hypertension rates increased for all maternal race and Hispanic-origin groups, age groups, and BMI categories, as well as by plurality, and for all states and the District of Columbia.

In 2024, variation in the rate of gestational hypertension was observed across race and Hispanic-origin groups. The rate for American Indian and Alaska Native mothers, the group with the highest rate of gestational hypertension, was nearly twice that for Asian mothers, the group with the lowest rate. By maternal age, the rate was lowest for mothers younger than age 20 and 30–34 and highest for mothers 40 and older. The rate of gestational hypertension rose with increasing maternal BMI. By plurality, the rate was nearly twice as high for mothers with a twin or higher-order multiple birth compared with that for mothers with a singleton birth. By state of residence, the rate ranged from 6.9% in New Jersey to 14.6% in Louisiana.

The finding of an increase in gestational hypertension over time is consistent with other data sources that have found an increase in hypertensive disorders during pregnancy, with one study of delivery hospitalizations noting that increases were largely driven by increases in pregnancy-associated hypertension in more recent years (4–6). The findings in this report of higher rates of gestational hypertension among women age 40 and older, those with overweight or obesity, and those with a multiple gestation pregnancy are consistent with established risk factors for hypertensive disorders during pregnancy (31,32). Also consistent with this report, one study among delivery hospitalizations found the highest rates of hypertensive disorders during pregnancy among Black and American Indian and Alaska Native women (5).

## Limitations

Underreporting of health conditions is considered a primary limitation of birth certificate data (33,34). Misreporting of information on the birth certificate may also affect some items (35). Two studies that examined data from the 2003 birth certificate revision for three vital statistics reporting areas found low or extremely low sensitivity (a measure of underreporting) for gestational hypertension across all three reporting areas, ranging from 20.0% to 50.0% (35,36). The false discovery rate (a measure of misreporting) was found to be moderate to high, ranging from 30.0%–38.5%, for the two reporting areas for which it could be calculated. Low sensitivity combined with high false discovery rates may indicate data quality concerns (35,36). However, the kappa scores (a more conservative measure of agreement) indicated fair to moderate agreement, ranging from 0.24 to 0.50 (35,36). It is important to note that since these data quality studies were conducted, several birth certificate data quality improvement efforts have been implemented; however, potential improvements in data quality have not been assessed.

Further, routine quality review of birth certificate data by NCHS suggests underreporting of gestational hypertension in some jurisdictions. For example, facility-level review of gestational hypertension data identified instances of large hospitals (those with over 1,000 births per year) that would be expected to report some incidence of gestational hypertension reporting fewer than expected or no cases. This reporting of lower-than-expected case numbers, based on comparisons with facilities of similar size within the same region over a period of 1 year or more, may suggest systemic underreporting of gestational hypertension by these facilities. Studies using birth certificate data to examine gestational hypertension should consider the possibility of underreporting and whether it may be differential based on other characteristics of the mother or the delivery.

Additionally, for birth certificate data on maternal hypertension, because of the way prepregnancy and gestational hypertension are defined and because they are considered to be mutually exclusive categories, explicit guidance on how to report hypertensive disorders during pregnancy that appear to meet the definitions for both (such as chronic hypertension with superimposed preeclampsia) is lacking.

## Conclusion

Hypertensive disorders during pregnancy are common pregnancy complications and are among the leading causes of maternal morbidity and mortality in the United States (4,6,7). This report on gestational hypertension shows increases in gestational hypertension overall and across all maternal age, race and Hispanic-origin, BMI, and plurality categories as well as U.S. states from 2016 to 2024. A primary advantage of birth certificate data is that information is collected on all women giving birth in the United States each year, allowing for analysis of both national trends and trends for smaller population groups, such as Native Hawaiian or Other Pacific Islander subgroups. However, gestational hypertension is most likely underreported on the birth certificate. Despite potential reporting issues, trends and patterns in gestational hypertension observed in this report are consistent with known risk factors and findings from other studies and provide opportunities to examine gestational hypertension among all women giving birth in the United States.

## Acknowledgments

This report was prepared in the Division of Vital Statistics (DVS) under the general direction of Paul Sutton, Director, DVS; Robert Anderson, Branch Chief, Statistical Analysis and Surveillance Branch; and the Perinatal Statistics and Research Team.

## References

1 Mayo Clinic. High blood pressure and pregnancy: Know the facts. 2022. Available from: https://www.mayoclinic.org/healthy-lifestyle/pregnancy-week-by-week/in-depth/pregnancy/art-20046098.
2 National Institutes of Health, National Heart, Lung, and Blood Institute. The Seventh Report of the Joint National Committee on Prevention, Detection, Evaluation, and Treatment of High Blood Pressure. 2004. Available from: https://www.nhlbi.nih.gov/files/docs/guidelines/jnc7full.pdf.
3 Khedagi AM, Bello NA. Hypertensive disorders of pregnancy. Cardiol Clin. 2021 Feb;39(1):77–90.33222817
4 U.S. Preventive Services Task Force. Screening for hypertensive disorders of pregnancy: U.S. Preventive Services Task Force Final Recommendation Statement. JAMA. 2023;330(11):1074–82.
5 Ford ND, Cox S, Ko JY, Ouyang L, Romero L, Colarusso T, et al. Hypertensive disorders in pregnancy and mortality at delivery hospitalization—United States, 2017–2019. MMWR Morb Mortal Wkly Rep 2022;71:585–91.35482575
6 Centers for Disease Control and Prevention. Pregnancy mortality surveillance system. 2025. Available from: https://www.cdc.gov/maternal-mortality/php/pregnancy-mortality-surveillance-data/index.html?cove-tab.
7 Xu JH, Czarny HN, Forde B, Warshak CR, DeFranco EA, Rossi RM. Severe maternal morbidity and mortality across subtypes of hypertensive disorders in pregnancy. Am J Obstet Gynecol MFM. 2026;8(1):101831. DOI: 10.1016/j.ajogmf.2025.101831.41203118
8 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2023. Natl Vital Stat Rep. 2025 Mar;74(1):1–87.
9 Centers for Disease Control and Prevention. High blood pressure during pregnancy. 2024. Available from: https://www.cdc.gov/high-blood-pressure/about/high-blood-pressure-during-pregnancy.html#:~:text=High.
10 Folk DM. Hypertensive disorders of pregnancy: Overview and current recommendations. J Midwifery Womens Health. 2018 May;63(3):289–300. DOI: 10.1111/jmwh.12725 .29764001
11 Garovic VD, White WM, Vaughan L, Saiki M, Parashuram S, Garcia-Valencia O, et al. Incidence and long-term outcomes of hypertensive disorders of pregnancy. J Am Coll Cardiol. 2020 May;75(18):2323–34.32381164
12 Farahi N, Oluyadi F, Dotson AB. Hypertensive disorders of pregnancy. Am Fam Physician. 2024 Mar;109(3):251–60.38574215
13 National Center for Health Statistics. 2003 revision of the U.S. Standard Certificate of Live Birth. 2003. Available from: https://www.cdc.gov/nchs/data/dvs/birth11-03final-ACC.pdf.
14 National Center for Health Statistics. Facility worksheet for the live birth certificate. 2016. Available from: https://www.cdc.gov/nchs/data/dvs/facility-worksheet-2016-508.pdf.
15 Whelton PK, Carey RM, Aronow WS, Casey DE Jr, Collins KJ, Dennison Himmelfarb C, et al. 2017 ACC/AHA/AAPA/ABC/ACPM/AGS/APhA/ASH/ASPC/NMA/PCNA Guideline for the prevention, detection, evaluation, and management of high blood pressure in adults: A report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Hypertension. 2018 Jun;71(6):1269–1324.
16 National Center for Health Statistics. User guide to the 2022 natality public use file. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2022.pdf.
17 Centers for Disease Control and Prevention. CDC WONDER. Births. Available from: https://wonder.cdc.gov/natality.html.
18 National Center for Health Statistics. Birth public use files. Available from: https://www.cdc.gov/nchs/data_access/vitalstatsonline.htm.
19 National Center for Health Statistics. User guide to the 2016 natality public use file. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2016.pdf.
20 National Center for Health Statistics. Guide to completing the facility worksheets for the certificate of live birth and report of fetal death (2003 revision). Available from: https://www.cdc.gov/nchs/data/dvs/GuidetoCompleteFacilityWks.pdf.
21 American College of Obstetricians and Gynecologists. Gestational hypertension and preeclampsia: ACOG Practice Bulletin, Number 222. Obstet Gynecol 2020 Jun;135(6):e237–60.
22 Cleveland Clinic. High blood pressure (hypertension) during pregnancy. Available from: https://my.clevelandclinic.org/health/diseases/4497-gestational-hypertension.
23 Melamed N, Ray JG, Hladunewich M, Cox B, Kingdom JC. Gestational hypertension and preeclampsia: Are they the same disease? J Obstet Gynaecol Can. 2014 Jul;36(7):642–7.25184984
24 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist 62(210):58782–90. 1997.
25 National Center for Health Statistics. User guide to the 2024 natality public use file. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2024.pdf.
26 National Heart, Lung, and Blood Institute. Clinical guidelines on the identification, evaluation, and treatment of obesity in adults—The evidence report. 1998.
27 National Center for Health Statistics. User guide to the 2010 natality public use file. 2011. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2010.pdf.
28 National Cancer Institute. Joinpoint Regression Program. Version 5.0.2 [software]. 2023.
29 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D, et al. National Center for Health Statistics data presentation standards for rates and counts. Vital Health Stat. 2023 Mar;2(200):1–26. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02-200.pdf.
30 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. Vital Health Stat. 2017 Aug;2(175): 1–22. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_175.pdf.
31 High blood pressure during pregnancy. Am Fam Physician. 2016 Jan;93(2):Online. PMID:26926416.26926416
32 Healthline. High blood pressure during pregnancy. 2025. Available from: https://www.healthline.com/health/high-blood-pressure-hypertension/during-pregnancy.
33 DiGuiseppe DL, Aron DC, Ranbom L, Harper DL, Rosenthal GE. Reliability of birth certificate data: A multi-hospital comparison to medical records information. Matern Child Health J. 2002 Sep;6(3):169–79.12236664
34 Roohan PJ, Josberger RE, Acar J, Dabir P, Feder HM, Gagliano PJ. Validation of birth certificate data in New York State. J Community Health. 2003 Oct;28(5):335–46.14535599
35 Martin JA, Wilson EC, Osterman MJK, Saadi EW, Sutton SR, Hamilton BE. Assessing the quality of medical and health data from the 2003 birth certificate revision: Results from two states. Natl Vital Stat Rep. 2013 Jul;62(2):1–20.
36 Gregory ECW, Martin JA, Argov EL, Osterman MJK. Assessing the quality of medical and health data from the 2003 birth certificate revision: Results from New York City. Natl Vital Stat Rep. 2019 Jun;68(8):1–20.

National Center for Health Statistics

Carolyn M. Greene, M.D., Acting Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science