# 75 Number 3 Infant Mortality in the United States, 2024: Data From the Period Linked Birth/Infant Death File

### Objectives

This report presents final 2024 infant mortality statistics by age at death, maternal race and Hispanic origin, maternal age, gestational age, leading causes of death, and maternal state of residence. Trends in infant mortality are also examined.

### Methods

Descriptive tabulations of data are presented and interpreted for infant deaths and infant mortality rates using the 2024 period linked birth/infant death file. The linked birth/infant death file is based on birth and death certificates registered in all 50 states and the District of Columbia.

### Results

A total of 20,048 infant deaths were reported in the United States in 2024, which was not significantly different from 2023 (20,162). The U.S. infant mortality rate was 5.52 infant deaths per 1,000 live births, which was not significantly different from the rate in 2023 (5.61). The change in the neonatal mortality rate from 3.65 in 2023 to 3.66 in 2024 was not significant. The postneonatal mortality rate declined 4.6% from 1.96 in 2023 to 1.87 in 2024. Changes in mortality rates for infants by maternal race and Hispanic origin and among Hispanic-origin subgroups were not significant. Infants of Black non-Hispanic women had the highest mortality rate (10.98) in 2024, followed by infants of American Indian and Alaska Native non-Hispanic (9.20) and Native Hawaiian or Other Pacific Islander non-Hispanic (7.90), Hispanic (4.88), White non-Hispanic (4.41), and Asian non-Hispanic (3.72) women. The mortality rate decreased from 2023 to 2024 for infants born at 39–40 weeks of gestation (1.64 to 1.55), but the rate change was not significantly different for other gestational age categories. Among the five leading causes of infant death in 2024, mortality rates for sudden infant death syndrome declined compared with 2023. Infant mortality rates by state for 2024 ranged from a low of 2.97 in New Hampshire to a high of 9.65 in Mississippi.

## Introduction

This report presents infant mortality statistics based on data from the 2024 period linked birth/infant death file. Infant mortality and mortality rates are described by age at death, maternal race and Hispanic origin, maternal age, gestational age, leading causes of death, and maternal state of residence. Infant mortality trends are also presented by selected characteristics. In the linked file, information from the death certificate is linked to information from the birth certificate for each infant younger than age 1 year who died in the 50 states, the District of Columbia, Puerto Rico, or Guam during 2024 (1). The purpose of the linkage is to use variables available from the birth certificate to conduct more detailed analyses of infant mortality patterns (2,3). The linked birth/infant death data set is also the preferred source for examining infant mortality by race and Hispanic origin. Infant mortality rates by race and Hispanic origin, based on maternal race and Hispanic origin, are more accurately measured from the birth certificate than the death certificate.

For 2024, linked birth/infant death data are not available for American Samoa, Commonwealth of the Northern Mariana Islands, and U.S. Virgin Islands. Some rates calculated from the mortality file differ from those published using the linked file. More details can be found elsewhere (1).

## Methods

Data shown in this report are based on birth and infant death certificates registered in all states, the District of Columbia, Puerto Rico, and Guam. As part of the Vital Statistics Cooperative Program, each state provides to the National Center for Health Statistics matching birth and death certificate numbers for each infant younger than age 1 year who died during 2024. Further discussion of the process of linking births and deaths occurring in different states and file production can be found in the Methodology section of the “User Guide to the 2024 Period/2023 Cohort Linked Birth/Infant Death Public Use File” (1).

The period linked file for 2017 marked the first data year for which the linked birth data for infant deaths for all 50 states and the District of Columbia were based on the 2003 revision of the U.S. Standard Certificate of Live Birth (4) and the first year for which national data on race and Hispanic-origin categories based on 1997 Office of Management and Budget standards became available (5).

In 2024, 98.8% of all infant death records were successfully linked to their corresponding birth records. These records were weighted to adjust for the 1.2% of infant death records that were not linked to their corresponding birth certificates (1) (Technical Notes).

Information for age and race of mother is imputed if it is not reported on the birth certificate. In 2024, race of mother was imputed for 8.4% of births (2,3). Mother’s age was imputed for 0.02% of births (2,3).

All race and Hispanic-origin data are based on single-race reporting and are consistent with the 1997 Office of Management and Budget standards and differ from the bridged-race categories shown in previous reports (5). Maternal race and Hispanic-origin categories presented are American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native), Asian non-Hispanic (subsequently, Asian), Black non-Hispanic (subsequently, Black), Native Hawaiian or Other Pacific Islander non-Hispanic (subsequently, Native Hawaiian or Other Pacific Islander), White non-Hispanic (subsequently, White), and Hispanic. Race and Hispanic origin are reported separately on the birth certificate. Data are shown in most cases for five specified Hispanic groups: Central and South American, Cuban, Dominican, Mexican, and Puerto Rican. Additional details on Hispanic origin are available elsewhere (3). Comparisons between 2024 and 2023 by race and Hispanic origin are made in this report. The 2003 revision of the U.S. Standard Certificate of Live Birth allows the reporting of five race categories for each parent (6)—either alone, as in single race, or in combination, as in more than one race or multiple races—in accordance with the 1997 revised Office of Management and Budget standards (5). Further details on race reporting are available elsewhere (3).

Cause-of-death statistics are classified in accordance with the International Statistical Classification of Diseases and Related Health Problems, 10th Revision (ICD–10) (1,7) (Technical Notes).

### Data by maternal and infant characteristics

This report presents descriptive tabulations of infant mortality data by a variety of maternal and infant characteristics. These tabulations are useful for understanding the basic relationships between risk factors and infant mortality, unadjusted for the possible effects of other variables. This report also presents several key risk factors for infant mortality: age at death, maternal race and Hispanic origin, maternal age, gestational age, leading causes of infant death, and maternal state of residence. For brevity, additional selected risk factors (sex, birthweight, plurality, and nativity [mother’s place of birth]) are presented in tables but are not discussed in this report.

Race and Hispanic origin—Infant mortality rates are presented by race and Hispanic origin of the mother. The linked file is useful for computing accurate infant mortality rates by these characteristics because the race and Hispanic origin of the mother from the birth certificate are used in both the numerator and denominator of the infant mortality rate. In contrast, for rates based on the vital statistics mortality file, race information for the denominator is the race of the mother as reported on the birth certificate, while race information for the numerator is the race of the decedent as reported on the death certificate (2,3,8). More detail on the reliability of race and Hispanic-origin data from the linked file compared with the mortality file is available elsewhere (8).

Statistical significance—Statements in the text have been tested for statistical significance, and a statement that a given infant mortality rate is higher or lower than another rate indicates that the rates are significantly different using a two-tailed z test at the alpha level of 0.05. Comparisons between state rates and the U.S. rate take into account each state’s contribution to the U.S. rate. As a result, each state rate is compared with a unique U.S. rate independent of the state’s contribution to the total U.S. rate. Information on the methods used to test for statistical significance and suppression standards, as well as information on differences between period and cohort data, the weighting of the linked file, state linkages of infant deaths with their corresponding birth certificates, maternal age, period of gestation, birthweight, and cause-of-death classification is also available (1) (Technical Notes).

## Results

### Trends in infant mortality and infant age at death

- In 2024, 20,048 infant deaths were reported in the United States, which was not significantly different from 2023 (20,162) (Figure 1, Table 1). The infant mortality rate was 5.52 deaths per 1,000 live births in 2024 and was not significantly different from the 2023 rate (5.61). The increase in the rate from 2021 (5.44) to 2022 (5.61) was the first increase since 2001 (6.84) to 2002 (6.95).
- The U.S. infant mortality rate has generally trended downward since 1995 (the first year that the period linked birth/infant death file was available) and is down 21% since 2002.
- The 2024 neonatal mortality rate (infant deaths at less than 28 days) of 3.66 was not significantly different from the rate in 2023 (3.65). The increase in the rate from 2021 (3.49) to 2022 (3.59) was the first since the increase from 2001 (4.54) to 2002 (4.67). The neonatal mortality rate has generally declined since 1995 and has decreased 22% since the last increase in 2002.
- The 2024 postneonatal mortality rate (infant deaths at 28 days or more) declined 4.6% to 1.87 from 1.96 in 2023. The rate increased from 2021 (1.95) to 2022 (2.02). The postneonatal mortality rate has also generally declined since 1995 and has decreased 18% since 2002 (2.28).

Figure 1 Infant, neonatal, and postneonatal mortality rates: United States, 1995–2024

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 1 is a line graph showing infant, neonatal and post-neonatal mortality rates from 1995 through 2024.

Table 1 Live births; infant, neonatal, and postneonatal deaths; and mortality rate: United States, 1995–2024, and by maternal race and Hispanic origin, 2017–2024

Race and Hispanic origin and year | Number | | | | Deaths per 1,000 live births
Race and Hispanic origin and year | Live births | Infant deaths | Neonatal deaths | Postneonatal deaths | Infant | Neonatal | Postneonatal
All race and Hispanic-origin groups
2024 | 3,628,934 | 20,048 | 13,272 | 6,776 | 5.52 | 3.66 | 1.87
2023 | 3,596,017 | 20,162 | 13,113 | 7,049 | 5.61 | 3.65 | 1.96
2022 | 3,667,758 | 20,577 | 13,158 | 7,419 | 5.61 | 3.59 | 2.02
2021 | 3,664,292 | 19,928 | 12,797 | 7,131 | 5.44 | 3.49 | 1.95
2020 | 3,613,647 | 19,578 | 12,866 | 6,712 | 5.42 | 3.56 | 1.86
2019 | 3,747,540 | 20,927 | 13,834 | 7,093 | 5.58 | 3.69 | 1.89
2018 | 3,791,712 | 21,498 | 14,329 | 7,169 | 5.67 | 3.78 | 1.89
2017 | 3,855,500 | 22,341 | 14,844 | 7,497 | 5.79 | 3.85 | 1.94
2016 | 3,945,875 | 23,157 | 15,303 | 7,854 | 5.87 | 3.88 | 1.99
2015 | 3,978,497 | 23,458 | 15,672 | 7,786 | 5.90 | 3.94 | 1.96
2014 | 3,988,076 | 23,211 | 15,737 | 7,474 | 5.82 | 3.95 | 1.87
2013 | 3,932,181 | 23,446 | 15,893 | 7,553 | 5.96 | 4.04 | 1.92
2012 | 3,952,841 | 23,654 | 15,887 | 7,767 | 5.98 | 4.02 | 1.96
2011 | 3,953,590 | 24,001 | 16,065 | 7,936 | 6.07 | 4.06 | 2.01
2010 | 3,999,386 | 24,572 | 16,193 | 8,379 | 6.14 | 4.05 | 2.10
2009 | 4,130,665 | 26,408 | 17,261 | 9,148 | 6.39 | 4.18 | 2.21
2008 | 4,247,726 | 28,075 | 18,238 | 9,837 | 6.61 | 4.29 | 2.32
2007 | 4,316,233 | 29,153 | 19,094 | 10,059 | 6.75 | 4.42 | 2.33
2006 | 4,265,593 | 28,509 | 19,041 | 9,468 | 6.68 | 4.46 | 2.22
2005 | 4,138,573 | 28,384 | 18,782 | 9,602 | 6.86 | 4.54 | 2.32
2004 | 4,112,055 | 27,860 | 18,602 | 9,258 | 6.78 | 4.52 | 2.25
2003 | 4,090,007 | 27,995 | 18,935 | 9,060 | 6.84 | 4.63 | 2.22
2002 | 4,021,825 | 27,970 | 18,791 | 9,179 | 6.95 | 4.67 | 2.28
2001 | 4,026,036 | 27,523 | 18,275 | 9,248 | 6.84 | 4.54 | 2.30
2000 | 4,058,882 | 27,961 | 18,733 | 9,227 | 6.89 | 4.62 | 2.27
1999 | 3,959,417 | 27,865 | 18,701 | 9,164 | 7.04 | 4.72 | 2.31
1998 | 3,941,553 | 28,325 | 18,915 | 9,410 | 7.19 | 4.80 | 2.39
1997 | 3,880,894 | 27,968 | 18,507 | 9,461 | 7.21 | 4.77 | 2.44
1996 | 3,891,494 | 28,419 | 18,556 | 9,863 | 7.30 | 4.77 | 2.53
1995 | 3,899,589 | 29,505 | 19,186 | 10,319 | 7.57 | 4.92 | 2.65
Non-Hispanic, single-race
American Indian and Alaska Native:
2024 | 24,021 | 221 | 128 | 93 | 9.20 | 5.33 | 3.87
2023 | 24,571 | 226 | 117 | 108 | 9.20 | 4.76 | 4.40
2022 | 25,721 | 233 | 135 | 98 | 9.06 | 5.25 | 3.81
2021 | 26,124 | 195 | 100 | 96 | 7.46 | 3.83 | 3.67
2020 | 26,813 | 206 | 102 | 104 | 7.68 | 3.80 | 3.88
2019 | 28,450 | 224 | 114 | 110 | 7.87 | 4.01 | 3.87
2018 | 29,092 | 237 | 120 | 117 | 8.15 | 4.12 | 4.02
2017 | 29,957 | 276 | 143 | 132 | 9.21 | 4.77 | 4.41
Asian:
2024 | 226,860 | 843 | 637 | 206 | 3.72 | 2.81 | 0.91
2023 | 215,738 | 742 | 542 | 199 | 3.44 | 2.51 | 0.92
2022 | 218,994 | 768 | 542 | 225 | 3.51 | 2.47 | 1.03
2021 | 213,813 | 788 | 594 | 193 | 3.69 | 2.78 | 0.90
2020 | 219,068 | 688 | 503 | 185 | 3.14 | 2.30 | 0.84
2019 | 238,769 | 806 | 602 | 204 | 3.38 | 2.52 | 0.85
2018 | 240,798 | 874 | 643 | 231 | 3.63 | 2.67 | 0.96
2017 | 249,250 | 943 | 675 | 268 | 3.78 | 2.71 | 1.08
Black:
2024 | 473,377 | 5,199 | 3,230 | 1,968 | 10.98 | 6.82 | 4.16
2023 | 491,494 | 5,374 | 3,260 | 2,114 | 10.93 | 6.63 | 4.30
2022 | 511,439 | 5,573 | 3,296 | 2,277 | 10.90 | 6.44 | 4.45
2021 | 517,889 | 5,463 | 3,291 | 2,172 | 10.55 | 6.35 | 4.19
2020 | 529,811 | 5,501 | 3,472 | 2,028 | 10.38 | 6.55 | 3.83
2019 | 548,075 | 5,821 | 3,754 | 2,067 | 10.62 | 6.85 | 3.77
2018 | 552,029 | 5,933 | 3,897 | 2,037 | 10.75 | 7.06 | 3.69
2017 | 560,715 | 6,152 | 4,012 | 2,140 | 10.97 | 7.16 | 3.82
Non-Hispanic, single race—Con.­
Native Hawaiian or Other Pacific Islander:
2024 | 10,375 | 82 | 39 | 42 | 7.90 | 3.76 | 4.05
2023 | 10,115 | 83 | 50 | 33 | 8.21 | 4.94 | 3.26
2022 | 10,122 | 86 | 48 | 38 | 8.50 | 4.74 | 3.75
2021 | 9,531 | 74 | 41 | 32 | 7.76 | 4.30 | 3.36
2020 | 9,626 | 69 | 41 | 27 | 7.17 | 4.26 | 2.80
2019 | 9,770 | 80 | 49 | 31 | 8.19 | 5.02 | 3.17
2018 | 9,476 | 89 | 51 | 38 | 9.39 | 5.38 | 4.01
2017 | 9,426 | 72 | 36 | 36 | 7.64 | 3.82 | 3.82
White:
2024 | 1,783,156 | 7,870 | 5,179 | 2,692 | 4.41 | 2.90 | 1.51
2023 | 1,787,051 | 8,008 | 5,127 | 2,881 | 4.48 | 2.87 | 1.61
2022 | 1,840,739 | 8,324 | 5,318 | 3,006 | 4.52 | 2.89 | 1.63
2021 | 1,887,656 | 8,236 | 5,251 | 2,984 | 4.36 | 2.78 | 1.58
2020 | 1,843,432 | 8,115 | 5,290 | 2,825 | 4.40 | 2.87 | 1.53
2019 | 1,915,912 | 8,603 | 5,589 | 3,014 | 4.49 | 2.92 | 1.57
2018 | 1,956,413 | 9,059 | 5,873 | 3,186 | 4.63 | 3.00 | 1.63
2017 | 1,992,461 | 9,306 | 6,061 | 3,246 | 4.67 | 3.04 | 1.63
Hispanic
2024 | 984,092 | 4,804 | 3,376 | 1,428 | 4.88 | 3.43 | 1.45
2023 | 945,200 | 4,750 | 3,356 | 1,394 | 5.03 | 3.55 | 1.47
2022 | 937,421 | 4,581 | 3,138 | 1,442 | 4.89 | 3.35 | 1.54
2021 | 885,916 | 4,246 | 2,899 | 1,347 | 4.79 | 3.27 | 1.52
2020 | 866,713 | 4,063 | 2,828 | 1,235 | 4.69 | 3.26 | 1.42
2019 | 886,467 | 4,462 | 3,091 | 1,371 | 5.03 | 3.49 | 1.55
2018 | 886,210 | 4,303 | 3,036 | 1,267 | 4.86 | 3.43 | 1.43
2017 | 898,764 | 4,583 | 3,198 | 1,383 | 5.10 | 3.56 | 1.54
Central and South American:
2024 | 231,723 | 1,038 | 739 | 299 | 4.48 | 3.19 | 1.29
2023 | 208,618 | 958 | 697 | 261 | 4.59 | 3.34 | 1.25
2022 | 207,843 | 907 | 652 | 255 | 4.36 | 3.14 | 1.23
2021 | 178,067 | 748 | 521 | 227 | 4.20 | 2.93 | 1.27
2020 | 169,811 | 659 | 470 | 189 | 3.88 | 2.77 | 1.11
2019 | 165,229 | 749 | 535 | 214 | 4.53 | 3.24 | 1.30
2018 | 147,430 | 592 | 438 | 154 | 4.02 | 2.97 | 1.04
2017 | 145,614 | 653 | 465 | 188 | 4.48 | 3.19 | 1.29
Cuban:
2024 | 32,315 | 136 | 96 | 40 | 4.21 | 2.97 | 1.24
2023 | 30,001 | 113 | 86 | 27 | 3.77 | 2.87 | 0.90
2022 | 26,390 | 104 | 65 | 39 | 3.94 | 2.46 | 1.48
2021 | 24,437 | 87 | 68 | 19 | 3.56 | 2.78 | *
2020 | 23,188 | 98 | 63 | 34 | 4.23 | 2.72 | 1.47
2019 | 23,668 | 98 | 65 | 33 | 4.14 | 2.75 | 1.39
2018 | 23,471 | 90 | 64 | 26 | 3.83 | 2.73 | 1.11
2017 | 23,362 | 93 | 69 | 24 | 3.98 | 2.95 | 1.03
Dominican:
2024 | 34,221 | 169 | 111 | 57 | 4.94 | 3.24 | 1.67
2023 | 33,575 | 154 | 106 | 48 | 4.59 | 3.16 | 1.43
2022 | 33,531 | 159 | 112 | 46 | 4.74 | 3.34 | 1.37
2021 | 33,373 | 109 | 68 | 41 | 3.27 | 2.04 | 1.23
2020 | 31,596 | 143 | 101 | 42 | 4.53 | 3.20 | 1.33
2019 | 32,483 | 153 | 111 | 42 | 4.71 | 3.42 | 1.29
Hispanic—Con.­
Mexican:
2024 | 521,149 | 2,529 | 1,795 | 734 | 4.85 | 3.44 | 1.41
2023 | 508,127 | 2,601 | 1,845 | 757 | 5.12 | 3.63 | 1.49
2022 | 510,194 | 2,442 | 1,688 | 754 | 4.79 | 3.31 | 1.48
2021 | 485,127 | 2,380 | 1,633 | 747 | 4.91 | 3.37 | 1.54
2020 | 480,531 | 2,264 | 1,586 | 678 | 4.71 | 3.30 | 1.41
2019 | 496,716 | 2,462 | 1,693 | 769 | 4.96 | 3.41 | 1.55
2018 | 495,831 | 2,426 | 1,690 | 736 | 4.89 | 3.41 | 1.48
2017 | 512,126 | 2,588 | 1,795 | 792 | 5.05 | 3.50 | 1.55
Puerto Rican:
2024 | 65,515 | 409 | 266 | 144 | 6.24 | 4.06 | 2.20
2023 | 66,203 | 426 | 282 | 144 | 6.43 | 4.26 | 2.18
2022 | 69,266 | 438 | 267 | 171 | 6.32 | 3.85 | 2.47
2021 | 70,729 | 428 | 278 | 151 | 6.05 | 3.93 | 2.13
2020 | 69,763 | 437 | 308 | 129 | 6.26 | 4.41 | 1.85
2019 | 70,950 | 438 | 294 | 144 | 6.17 | 4.14 | 2.03
2018 | 71,614 | 402 | 290 | 112 | 5.61 | 4.05 | 1.56
2017 | 70,813 | 459 | 307 | 151 | 6.48 | 4.34 | 2.13

* Estimate does not meet National Center for Health Statistics standards of reliability.

NOTES: Infant deaths are weighted to adjust for the 1.2% of infant death records not linked to their corresponding birth certificates. The neonatal and postneonatal mortality rates combined may not exactly add to totals due to rounding. People of Hispanic origin may be of any race. Data for infants of Dominican women are available starting with the 2019 period linked birth/infant death data files.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Race and Hispanic origin

- Mortality rates did not change significantly from 2023 to 2024 for infants of women of any of the race and Hispanic-origin groups: American Indian and Alaska Native (9.20 infant deaths per 1,000 live births in both 2023 and 2024), Asian (3.44 to 3.72), Black (10.93 to 10.98), Native Hawaiian or Other Pacific Islander (8.21 to 7.90), White (4.48 to 4.41), and Hispanic (5.03 to 4.88) (Tables 1 and 2, Figure 2).
- Mortality rates did not change significantly from 2023 to 2024 for infants of women in Hispanic-origin subgroups: Central and South American (4.59 to 4.48), Cuban (3.77 to 4.21), Dominican (4.59 to 4.94), Mexican (5.12 to 4.85), and Puerto Rican (6.43 to 6.24).
- In 2024, infant mortality continued to vary by race: Infants of Black women had the highest mortality rate (10.98), followed by infants of American Indian and Alaska Native and Native Hawaiian or Other Pacific Islander (9.20 and 7.90, respectively), Hispanic (4.88), White (4.41), and Asian (3.72) women.
- Infants of Black women had a higher neonatal mortality rate in 2024 (6.82) than infants of American Indian and Alaska Native (5.33), Native Hawaiian or Other Pacific Islander (3.76), Hispanic (3.43), White (2.90), and Asian (2.81) women (Table 2).
- In 2024, postneonatal mortality rates were higher for infants of Black (4.16), Native Hawaiian or Other Pacific Islander (4.05), and American Indian and Alaska Native (3.87) women than for infants of White (1.51), Hispanic (1.45), and Asian (0.91) women.
- Among Hispanic-origin subgroups in 2024, the mortality rate for infants of Puerto Rican women (6.24) was higher than rates for infants of Dominican (4.94), Mexican (4.85), Central and South American (4.48), and Cuban (4.21) women.

Figure 2 Infant mortality rate, by maternal race and Hispanic origin: United States, 2023 and 2024

^1^People of Hispanic origin may be of any race.

NOTE: No significant differences were seen in rates from 2023 to 2024.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 2 is a bar graph showing infant mortality rates by maternal race and Hispanic origin for 2023 and 2024.

Table 2 Infant mortality rate, live births, and infant deaths, by selected characteristics and maternal race and Hispanic origin: United States, 2024

Characteristic | Total | Non-Hispanic | | | | | Hispanic
Characteristic | Total | American Indian and Alaska Native^1^ | Asian | Black | Native Hawaiian or Other Pacific Islander | White | Total^2^ | Central and South American | Cuban | Dominican | Mexican | Puerto Rican
| Infant deaths per 1,000 live births in specified group
Total | 5.52 | 9.20 | 3.72 | 10.98 | 7.90 | 4.41 | 4.88 | 4.48 | 4.21 | 4.94 | 4.85 | 6.24
Age at death (days)
Total neonatal | 3.66 | 5.33 | 2.81 | 6.82 | 3.76 | 2.90 | 3.43 | 3.19 | 2.97 | 3.24 | 3.44 | 4.06
Early neonatal (less than 7) | 2.87 | 3.79 | 2.22 | 5.31 | 2.80 | 2.27 | 2.72 | 2.48 | 2.17 | 2.60 | 2.72 | 3.30
Late neonatal (7–27) | 0.79 | 1.50 | 0.59 | 1.51 | 0.96 | 0.64 | 0.71 | 0.72 | 0.80 | 0.64 | 0.72 | 0.75
Postneonatal (28–364) | 1.87 | 3.87 | 0.91 | 4.16 | 4.05 | 1.51 | 1.45 | 1.29 | 1.24 | 1.67 | 1.41 | 2.20
Sex
Male | 5.88 | 11.05 | 3.85 | 11.78 | 9.23 | 4.73 | 5.10 | 4.64 | 4.48 | 4.77 | 5.02 | 6.98
Female | 5.15 | 7.23 | 3.59 | 10.15 | 6.31 | 4.08 | 4.65 | 4.32 | 3.92 | 5.11 | 4.68 | 5.51
Period of gestation (weeks)
Less than 37 | 34.49 | 41.58 | 28.70 | 50.68 | 37.72 | 28.22 | 32.83 | 31.46 | 30.42 | 34.01 | 33.01 | 35.76
Less than 34 | 108.14 | 114.53 | 96.88 | 131.67 | 103.06 | 93.28 | 107.37 | 105.12 | 97.04 | 98.69 | 109.58 | 113.41
Less than 28 | 368.75 | 383.72 | 357.26 | 366.01 | 376.62 | 371.48 | 355.88 | 350.88 | 306.60 | 322.58 | 359.45 | 385.66
28–31 | 42.78 | 62.99 | 28.68 | 43.55 | * | 43.87 | 41.15 | 48.17 | 44.44 | * | 40.68 | 32.56
32–33 | 20.04 | 28.50 | 14.60 | 24.38 | * | 18.01 | 19.70 | 16.74 | * | * | 22.01 | 11.53
34–36 | 8.41 | 14.43 | 5.79 | 11.48 | 12.77 | 7.86 | 7.39 | 7.42 | 5.35 | 8.97 | 7.26 | 7.39
37–41 | 2.09 | 4.45 | 1.15 | 3.94 | 3.54 | 1.86 | 1.72 | 1.61 | 1.38 | 1.53 | 1.69 | 2.34
37–38 | 3.13 | 6.53 | 1.68 | 5.15 | 4.50 | 2.90 | 2.56 | 2.27 | 2.81 | 2.52 | 2.49 | 3.54
39–40 | 1.55 | 3.07 | 0.85 | 3.13 | 3.05 | 1.36 | 1.26 | 1.26 | 0.70 | 0.89 | 1.27 | 1.65
41 | 1.67 | * | * | 3.08 | * | 1.55 | 1.45 | 1.39 | * | * | 1.33 | *
42 or more | 4.27 | * | * | * | * | 3.65 | 6.70 | * | * | * | * | *
Birthweight (grams)
Less than 2,500 | 42.40 | 54.13 | 28.50 | 50.95 | 45.69 | 38.18 | 42.70 | 42.52 | 42.54 | 38.40 | 43.33 | 42.77
Less than 1,500 | 200.13 | 220.67 | 173.05 | 206.82 | 195.27 | 191.23 | 202.29 | 195.95 | 188.26 | 171.70 | 207.13 | 211.34
1,500–2,499 | 12.74 | 21.41 | 7.39 | 13.93 | 14.71 | 12.63 | 12.56 | 13.71 | 11.84 | 10.33 | 12.56 | 11.56
2,500 or more | 2.03 | 4.67 | 1.05 | 3.79 | 3.83 | 1.84 | 1.63 | 1.46 | 1.17 | 1.64 | 1.64 | 2.09
2,500–4,499 | 2.03 | 4.60 | 1.05 | 3.78 | 3.79 | 1.84 | 1.62 | 1.46 | 1.18 | 1.65 | 1.63 | 2.11
4,500 or more | 2.34 | * | * | 4.75 | * | 2.01 | 2.10 | * | * | * | 2.99 | *
Plurality
Single births | 5.04 | 8.73 | 3.36 | 9.87 | 7.41 | 4.05 | 4.51 | 4.13 | 3.85 | 4.70 | 4.50 | 5.79
Twin births | 20.09 | 25.48 | 17.00 | 34.87 | * | 14.75 | 19.11 | 20.51 | 14.12 | 10.61 | 18.74 | 17.65
Triplet and higher-order births | 56.03 | * | * | 68.97 | * | 44.48 | 70.10 | * | * | * | 48.58 | *
Age of mother | Infant deaths per 1,000 live births in specified group—Con.
Younger than 15 | 18.53 | * | * | 25.86 | * | * | 12.74 | * | * | * | * | *
15–19 | 9.78 | 9.61 | * | 14.67 | * | 9.72 | 7.26 | 5.35 | * | * | 7.73 | 12.11
20–24 | 6.89 | 8.96 | 6.36 | 12.81 | 8.92 | 5.98 | 5.06 | 4.46 | 5.07 | 5.02 | 4.87 | 6.70
25–29 | 5.22 | 8.08 | 4.14 | 10.48 | 8.51 | 4.17 | 4.46 | 3.97 | 3.39 | 6.13 | 4.41 | 6.02
30–34 | 4.65 | 9.00 | 3.22 | 9.61 | 7.67 | 3.71 | 4.44 | 4.27 | 3.96 | 3.63 | 4.44 | 5.77
35–39 | 4.90 | 9.44 | 3.49 | 10.09 | * | 3.88 | 4.60 | 4.47 | 4.51 | 4.22 | 4.62 | 4.33
40–54 | 6.96 | 21.77 | 4.60 | 12.05 | * | 5.39 | 7.21 | 7.20 | * | 7.43 | 7.30 | 6.35
Mother’s place of birth
50 states or District of Columbia | 5.71 | 9.28 | 3.87 | 11.62 | 8.93 | 4.43 | 5.17 | 4.82 | 5.27 | 5.19 | 4.95 | 6.15
Elsewhere | 4.67 | * | 3.62 | 7.97 | 6.81 | 3.74 | 4.54 | 4.41 | 3.69 | 4.77 | 4.64 | 6.30
| Live births
Total | 3,628,934 | 24,021 | 226,860 | 473,377 | 10,375 | 1,783,156 | 984,092 | 231,723 | 32,315 | 34,221 | 521,149 | 65,515
Sex
Male | 1,853,969 | 12,399 | 116,716 | 240,537 | 5,306 | 913,082 | 501,012 | 117,738 | 16,506 | 17,383 | 265,526 | 33,381
Female | 1,774,965 | 11,622 | 110,144 | 232,840 | 5,069 | 870,074 | 483,080 | 113,985 | 15,809 | 16,838 | 255,623 | 32,134
Period of gestation (weeks)
Less than 37 | 377,204 | 3,030 | 20,764 | 70,231 | 1,299 | 168,964 | 98,970 | 21,998 | 3,090 | 3,558 | 52,072 | 7,579
Less than 34 | 98,629 | 812 | 5,223 | 22,913 | 359 | 40,278 | 25,175 | 5,413 | 845 | 993 | 13,104 | 2,028
Less than 28 | 22,774 | 172 | 1,184 | 6,773 | 77 | 7,602 | 6,016 | 1,254 | 212 | 248 | 3,152 | 516
28–31 | 32,893 | 254 | 1,778 | 7,485 | 111 | 13,358 | 8,602 | 1,889 | 270 | 353 | 4,499 | 645
32–33 | 42,962 | 386 | 2,261 | 8,655 | 171 | 19,318 | 10,557 | 2,270 | 363 | 392 | 5,453 | 867
34–36 | 278,575 | 2,218 | 15,541 | 47,318 | 940 | 128,686 | 73,795 | 16,585 | 2,245 | 2,565 | 38,968 | 5,551
37–41 | 3,238,129 | 20,878 | 205,810 | 401,430 | 9,031 | 1,606,388 | 882,739 | 209,009 | 29,055 | 30,626 | 468,049 | 57,793
37–38 | 1,096,713 | 7,960 | 72,673 | 160,042 | 3,332 | 512,225 | 303,261 | 70,149 | 9,240 | 10,337 | 161,602 | 20,639
39–40 | 1,979,343 | 12,069 | 126,204 | 225,481 | 5,238 | 1,002,564 | 539,534 | 128,806 | 18,630 | 19,018 | 285,443 | 34,631
41 | 162,073 | 849 | 6,933 | 15,907 | 461 | 91,599 | 39,944 | 10,054 | 1,185 | 1,271 | 21,004 | 2,523
42 or more | 9,144 | 61 | 139 | 995 | 26 | 6,021 | 1,492 | 377 | 40 | 28 | 812 | 86
Not stated | 4,457 | 52 | 147 | 721 | 19 | 1,783 | 891 | 339 | 130 | * | 216 | 57
Birthweight (grams)
Less than 2,500 | 310,080 | 2,180 | 21,717 | 71,339 | 985 | 124,490 | 77,447 | 16,886 | 2,351 | 3,047 | 39,927 | 6,663
Less than 1,500 | 49,074 | 358 | 2,768 | 13,693 | 169 | 17,811 | 12,304 | 2,664 | 409 | 530 | 6,315 | 1,041
1,500–2,499 | 261,006 | 1,822 | 18,949 | 57,646 | 816 | 106,679 | 65,143 | 14,222 | 1,942 | 2,517 | 33,612 | 5,622
2,500 or more | 3,317,928 | 21,838 | 205,129 | 401,968 | 9,390 | 1,658,442 | 906,585 | 214,819 | 29,963 | 31,171 | 481,203 | 58,844
2,500–4,499 | 3,285,410 | 21,511 | 204,262 | 399,441 | 9,247 | 1,638,565 | 898,983 | 213,258 | 29,638 | 30,952 | 476,850 | 58,415
4,500 or more | 32,518 | 327 | 867 | 2,527 | 143 | 19,877 | 7,602 | 1,561 | 325 | 219 | 4,353 | 429
Not stated | 926 | * | 14 | 70 | – | 224 | 60 | 18 | * | * | 19 | *
Plurality | Live births—Con.
Single births | 3,517,151 | 23,373 | 221,449 | 452,981 | 10,118 | 1,726,015 | 960,531 | 227,036 | 31,439 | 33,158 | 508,894 | 63,416
Twin births | 109,195 | 628 | 5,294 | 19,874 | 254 | 55,792 | 23,076 | 4,633 | 850 | 1,037 | 12,008 | 2,040
Triplet and higher-order births | 2,588 | 20 | 117 | 522 | * | 1,349 | 485 | 54 | 26 | 26 | 247 | 59
Age of mother
Younger than 15 | 1,727 | 30 | 11 | 464 | * | 341 | 785 | 286 | – | 14 | 385 | 39
15–19 | 137,273 | 1,769 | 888 | 26,450 | 453 | 43,508 | 57,700 | 14,755 | 687 | 1,129 | 31,581 | 3,632
20–24 | 611,800 | 6,029 | 9,126 | 96,149 | 2,467 | 257,486 | 216,365 | 48,431 | 5,327 | 6,377 | 120,247 | 14,777
25–29 | 990,817 | 6,807 | 41,742 | 124,237 | 3,055 | 497,706 | 283,198 | 63,951 | 9,154 | 9,462 | 153,597 | 19,104
30–34 | 1,112,409 | 5,776 | 93,782 | 128,145 | 2,607 | 593,646 | 253,011 | 58,786 | 10,105 | 9,931 | 131,226 | 17,144
35–39 | 622,517 | 2,967 | 64,989 | 75,600 | 1,391 | 320,734 | 136,132 | 35,103 | 5,760 | 5,692 | 66,436 | 8,772
40–54 | 152,391 | 643 | 16,322 | 22,332 | 398 | 69,735 | 36,901 | 10,411 | 1,282 | 1,616 | 17,677 | 2,047
Mother’s place of birth
50 states or District of Columbia | 2,734,001 | 23,597 | 53,529 | 375,335 | 3,806 | 1,656,820 | 514,060 | 35,485 | 10,620 | 10,406 | 339,716 | 47,779
Elsewhere | 887,378 | 378 | 172,744 | 96,280 | 6,463 | 123,815 | 468,825 | 195,987 | 21,676 | 23,702 | 181,014 | 17,619
Not stated | 7,555 | 46 | 587 | 1,762 | 106 | 2,521 | 1,207 | 251 | 19 | 113 | 419 | 117
| Infant deaths
Total | 20,048 | 221 | 843 | 5,199 | 82 | 7,870 | 4,804 | 1,038 | 136 | 169 | 2,529 | 409
Age at death (days)
Total neonatal | 13,272 | 128 | 637 | 3,230 | 39 | 5,179 | 3,376 | 739 | 96 | 111 | 1,795 | 266
Early neonatal (less than 7) | 10,410 | 91 | 503 | 2,515 | 29 | 4,040 | 2,679 | 574 | 70 | 89 | 1,419 | 216
Late neonatal (7–27) | 2,862 | 36 | 134 | 715 | 10 | 1,138 | 697 | 166 | 26 | 22 | 375 | 49
Postneonatal (28–364) | 6,776 | 93 | 206 | 1,968 | 42 | 2,692 | 1,428 | 299 | 40 | 57 | 734 | 144
Sex
Male | 10,909 | 137 | 449 | 2,834 | 49 | 4,317 | 2,557 | 546 | 74 | 83 | 1,333 | 233
Female | 9,139 | 84 | 395 | 2,364 | 32 | 3,553 | 2,247 | 492 | 62 | 86 | 1,196 | 177
Period of gestation (weeks) | Infant deaths—Con.
Less than 37 | 13,009 | 126 | 596 | 3,559 | 49 | 4,768 | 3,249 | 692 | 94 | 121 | 1,719 | 271
Less than 34 | 10,666 | 93 | 506 | 3,017 | 37 | 3,757 | 2,703 | 569 | 82 | 98 | 1,436 | 230
Less than 28 | 8,398 | 66 | 423 | 2,479 | 29 | 2,824 | 2,141 | 440 | 65 | 80 | 1,133 | 199
28–31 | 1,407 | 16 | 51 | 326 | * | 586 | 354 | 91 | 12 | * | 183 | 21
32–33 | 861 | 11 | 33 | 211 | * | 348 | 208 | 38 | * | * | 120 | 10
34–36 | 2,344 | 32 | 90 | 543 | 12 | 1,011 | 545 | 123 | 12 | 23 | 283 | 41
37–41 | 6,779 | 93 | 237 | 1,580 | 32 | 2,993 | 1,514 | 336 | 40 | 47 | 792 | 135
37–38 | 3,435 | 52 | 122 | 825 | 15 | 1,485 | 776 | 159 | 26 | 26 | 402 | 73
39–40 | 3,073 | 37 | 107 | 706 | 16 | 1,367 | 680 | 162 | 13 | 17 | 362 | 57
41 | 271 | * | * | 49 | * | 142 | 58 | 14 | * | * | 28 | *
42 or more | 39 | * | – | * | – | 22 | 10 | * | – | – | * | *
Not stated | 220 | * | 10 | 56 | – | 87 | 32 | * | * | – | 11 | *
Birthweight (grams)
Less than 2,500 | 13,147 | 118 | 619 | 3,635 | 45 | 4,753 | 3,307 | 718 | 100 | 117 | 1,730 | 285
Less than 1,500 | 9,821 | 79 | 479 | 2,832 | 33 | 3,406 | 2,489 | 522 | 77 | 91 | 1,308 | 220
1,500–2,499 | 3,326 | 39 | 140 | 803 | 12 | 1,347 | 818 | 195 | 23 | 26 | 422 | 65
2,500 or more | 6,741 | 102 | 216 | 1,523 | 36 | 3,057 | 1,474 | 313 | 35 | 51 | 791 | 123
2,500–4,499 | 6,665 | 99 | 214 | 1,511 | 35 | 3,017 | 1,457 | 312 | 35 | 51 | 778 | 123
4,500 or more | 76 | * | * | 12 | * | 40 | 16 | * | – | – | 13 | –
Not stated | 161 | * | * | 40 | – | 61 | 23 | * | * | – | * | *
Plurality
Single births | 17,709 | 204 | 745 | 4,469 | 75 | 6,987 | 4,329 | 938 | 121 | 156 | 2,292 | 367
Twin births | 2,194 | 16 | 90 | 693 | * | 823 | 441 | 95 | 12 | 11 | 225 | 36
Triplet and higher-order births | 145 | – | * | 36 | – | 60 | 34 | * | * | * | 12 | *
Age of mother
Younger than 15 | 32 | * | * | 12 | – | * | 10 | * | – | – | * | *
15–19 | 1,343 | 17 | * | 388 | – | 423 | 419 | 79 | * | * | 244 | 44
20–24 | 4,216 | 54 | 58 | 1,232 | 22 | 1,539 | 1,095 | 216 | 27 | 32 | 586 | 99
25–29 | 5,174 | 55 | 173 | 1,302 | 26 | 2,077 | 1,263 | 254 | 31 | 58 | 678 | 115
30–34 | 5,172 | 52 | 302 | 1,231 | 20 | 2,204 | 1,124 | 251 | 40 | 36 | 583 | 99
35–39 | 3,050 | 28 | 227 | 763 | * | 1,246 | 626 | 157 | 26 | 24 | 307 | 38
40–54 | 1,061 | 14 | 75 | 269 | * | 376 | 266 | 75 | * | 12 | 129 | 13
Mother’s place of birth | Infant deaths—Con.
50 states or District of Columbia | 15,622 | 219 | 207 | 4,361 | 34 | 7,342 | 2,657 | 171 | 56 | 54 | 1,683 | 294
Elsewhere | 4,144 | * | 626 | 767 | 44 | 463 | 2,127 | 864 | 80 | 113 | 839 | 111
Not stated | 282 | * | 10 | 71 | * | 66 | 20 | * | – | * | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

– Quantity zero.

^1^Includes Aleut and Eskimo people.

^2^Includes other and unknown Hispanic origin not stated, not shown separately.

NOTES: Infant deaths are weighted so numbers may not exactly add to totals due to rounding. Not stated responses were included in totals but not distributed among groups for rate computations. Race and Hispanic origin are reported separately on birth certificates. Race categories are consistent with the 1997 Office of Management and Budget standards. People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Maternal age

- From 2023 to 2024, the mortality rate declined for infants of women ages 20–24, from 7.23 infant deaths per 1,000 live births to 6.89 (Figure 3, Table 2).
- Mortality rates did not change significantly from 2023 to 2024 for infants of females younger than 15 (20.95 to 18.53), 15–19 (10.44 to 9.78), 25–29 (5.24 to 5.22), 30–34 (4.59 to 4.65), 35–39 (4.94 to 4.90), and 40 and older (6.77 to 6.96).
- In 2024, mortality rates were highest for infants of females younger than 15 (18.53), decreased to a low of 4.65 for infants of women ages 30–34, and then increased to 6.96 for infants of women 40 and older.

Figure 3 Infant mortality rate, by maternal age: United States, 2023 and 2024

^1^Significantly different from 2023 (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 3 is a bar graph showing infant mortality rates by maternal age for 2023 and 2024.

### Gestational age

- The mortality rate declined for infants born at 39–40 weeks (1.64 infant deaths per 1,000 live births to 1.55) but did not change significantly for the other gestational age categories from 2023 to 2024: preterm (less than 37 weeks of gestation) (34.74 to 34.49), early preterm (less than 34 weeks of gestation) (107.87 to 108.14), late preterm (34–36 weeks) (8.31 to 8.41), term (37–41 weeks) (2.16 to 2.09), or post-term (42 weeks or more) (3.66 to 4.27) (Table, Table 2).
- In 2024, about two-thirds of all infant deaths (66%) occurred among infants born preterm (less than 37 weeks of gestation), which was essentially unchanged from 2023 (65%).

Table Infant mortality rate, by gestational age: United States, 2015–2024

Year | Less than 32 weeks | 32–33 weeks | 34–36 weeks | 37–41 weeks | 42 weeks or more
| Deaths per 1,000 live births
2024 | 176.14 | 20.04 | 8.41 | 2.09 | 4.27
2023 | 174.28 | 21.04 | 8.31 | 2.16 | 3.66
2022 | 175.18 | 21.05 | 8.29 | 2.18 | 4.23
2021 | 167.39 | 19.35 | 8.11 | 2.08 | 3.79
2020 | 175.88 | 20.11 | 7.92 | 2.04 | 4.17
2019 | 180.40 | 19.21 | 8.21 | 2.03 | 5.72
2018 | 185.79 | 21.95 | 8.21 | 2.05 | 5.39
2017 | 187.56 | 20.50 | 8.50 | 2.10 | 3.98
2016 | 190.15 | 20.12 | 8.65 | 2.19 | 4.31
2015 | 193.54 | 20.79 | 8.76 | 2.17 | 4.20

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Leading causes of infant death

- In 2024, the five leading causes of all infant deaths were the same as those in 2023: congenital malformations (20.4% of infant deaths), disorders related to short gestation and low birth weight (14.6%), sudden infant death syndrome (SIDS) (6.7%), unintentional injuries (6.2%), and maternal complications (6.0%) (Table 3).
- From 2023 to 2024, the infant mortality rate for SIDS declined (from 40.2 infant deaths per 100,000 live births to 37.2). Infant mortality rates for congenital malformations (112.1 to 112.7), disorders related to short gestation and low birth weight (81.4 to 81.2), unintentional injuries (35.8 to 34.0), and maternal complications (31.9 to 33.0) did not change significantly.
- Congenital malformations was the leading cause of death for infants of women in most race and Hispanic-origin groups: American Indian and Alaska Native (166.5), Asian (66.1), Native Hawaiian or Other Pacific Islander (154.2), White (100.7), and Hispanic (123.5) in 2024 (Table 4).
- In 2024, disorders related to short gestation and low birth weight was the leading cause of death for infants of Black women (202.4).

Table 3 Infant deaths, percentage of deaths, and infant mortality rate, by five leading causes of infant death: United States, 2010–2024

Year | Congenital malformations(Q00–Q99) | | | Short gestation and low birth weight, not elsewhere classified (P07) | | | Sudden infant death syndrome(R95) | | | Accidents (unintentional injures) (V01–X59) | | | Maternal complications of pregnancy (P01)
Year | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births)
2024 | 4,091 | 20.4 | 112.7 | 2,945 | 14.6 | 81.2 | 1,350 | 6.7 | 37.2 | 1,235 | 6.2 | 34.0 | 1,199 | 6.0 | 33.0
2023 | 4,030 | 20.0 | 112.1 | 2,927 | 14.5 | 81.4 | 1,446 | 7.2 | 40.2 | 1,288 | 6.4 | 35.8 | 1,146 | 5.7 | 31.9
2022 | 4,004 | 19.5 | 109.2 | 2,884 | 14.0 | 78.6 | 1,531 | 7.4 | 41.7 | 1,351 | 6.6 | 36.8 | 1,213 | 5.9 | 33.1
2021 | 3,990 | 20.0 | 108.9 | 2,957 | 14.8 | 80.7 | 1,458 | 7.3 | 39.8 | 1,300 | 6.5 | 35.5 | 1,113 | 5.6 | 30.4
2020 | 4,047 | 20.7 | 112.0 | 3,152 | 16.1 | 87.2 | 1,386 | 7.1 | 38.4 | 1,192 | 6.1 | 33.0 | 1,115 | 5.7 | 30.9
2019 | 4,313 | 20.6 | 115.1 | 3,460 | 16.5 | 92.3 | 1,251 | 6.0 | 33.4 | 1,264 | 6.0 | 33.7 | 1,250 | 6.0 | 33.4
2018 | 4,501 | 20.9 | 118.7 | 3,683 | 17.1 | 97.1 | 1,331 | 6.2 | 35.1 | 1,169 | 5.4 | 30.8 | 1,371 | 6.4 | 36.2
2017 | 4,596 | 20.6 | 119.2 | 3,757 | 16.8 | 97.4 | 1,360 | 6.1 | 35.3 | 1,313 | 5.9 | 34.1 | 1,436 | 6.4 | 37.2
2016 | 4,823 | 20.8 | 122.2 | 3,926 | 17.0 | 99.5 | 1,498 | 6.5 | 38.0 | 1,217 | 5.3 | 30.8 | 1,407 | 6.1 | 35.7
2015 | 4,847 | 20.7 | 121.8 | 4,087 | 17.4 | 102.7 | 1,567 | 6.7 | 39.4 | 1,289 | 5.5 | 32.4 | 1,527 | 6.5 | 38.4
2014 | 4,754 | 20.5 | 119.2 | 4,172 | 18.0 | 104.6 | 1,541 | 6.6 | 38.6 | 1,163 | 5.0 | 29.2 | 1,580 | 6.8 | 39.6
2013 | 4,778 | 20.4 | 121.5 | 4,213 | 18.0 | 107.1 | 1,561 | 6.7 | 39.7 | 1,150 | 4.9 | 29.2 | 1,597 | 6.8 | 40.6
2012 | 4,967 | 21.0 | 125.7 | 4,214 | 17.8 | 106.6 | 1,676 | 7.1 | 42.4 | 1,163 | 4.9 | 29.4 | 1,518 | 6.4 | 38.4
2011 | 5,016 | 20.9 | 126.9 | 4,115 | 17.1 | 104.1 | 1,905 | 7.9 | 48.2 | 1,167 | 4.9 | 29.5 | 1,598 | 6.7 | 40.4
2010 | 5,115 | 20.8 | 127.9 | 4,151 | 16.9 | 103.8 | 2,058 | 8.4 | 51.5 | 1,107 | 4.5 | 27.7 | 1,563 | 6.4 | 39.1

NOTE: The five leading causes of death (based on International Classification of Diseases, 10th Revision, 1992) were the same from 2010–2024, but ranking changed in 2020 and later years compared with previous years.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Table 4 Infant deaths and mortality rate for the five leading causes of infant death, by maternal race and Hispanic origin: United States, 2024

[Rates are per 100,000 live births in specified group]

| | | | Non-Hispanic
Cause of death (based on International Classification of Diseases, 10th Revision, 1992) | All races | | | American Indian and Alaska Native | | | Asian^1^ | | | Black | | | Native Hawaiian or Other Pacific Islander | | | White
Cause of death (based on International Classification of Diseases, 10th Revision, 1992) | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate
All causes | … | 20,048 | 552.4 | … | 221 | 920.0 | … | 843 | 371.6 | … | 5,199 | 1,098.3 | … | 82 | 790.4 | … | 7,870 | 441.4
Congenital malformations, deformations, and chromosomalabnormalities(Q00–Q99) | 1 | 4,091 | 112.7 | 1 | 40 | 166.5 | 1 | 150 | 66.1 | 2 | 676 | 142.8 | 1 | 16 | 154.2 | 1 | 1,795 | 100.7
Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 2 | 2,945 | 81.2 | 2 | 30 | 124.9 | 2 | 143 | 63.0 | 1 | 958 | 202.4 | 2 | 10 | 96.4 | 2 | 929 | 52.1
Sudden infant death syndrome(R95) | 3 | 1,350 | 37.2 | 4 | 21 | 87.4 | 6 | 28 | 12.3 | 3 | 400 | 84.5 | … | * | * | 3 | 562 | 31.5
Accidents (unintentional injuries)(V01–X59) | 4 | 1,235 | 34.0 | 3 | 24 | 99.9 | 9 | 18 | 7.9 | 4 | 394 | 83.2 | … | * | * | 4 | 527 | 29.6
Newborn affected by maternal complications of pregnancy(P01) | 5 | 1,199 | 33.0 | 5 | 12 | 50.0 | 3 | 61 | 26.9 | 5 | 323 | 68.2 | … | * | * | 5 | 392 | 22.0
Cause of death (based on International Classification of Diseases, 10th Revision, 1992) | Total Hispanic | | | Central and South American^2^ | | | Cuban | | | Dominican | | | Mexican | | | Puerto Rican
Cause of death (based on International Classification of Diseases, 10th Revision, 1992) | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate
All causes | … | 4,804 | 488.2 | … | 1,038 | 447.9 | … | 136 | 420.9 | … | 169 | 493.8 | … | 2529 | 485.3 | … | 409 | 624.3
Congenital malformations, deformations, and chromosomal abnormalities(Q00–Q99) | 1 | 1,215 | 123.5 | 1 | 303 | 130.8 | 1 | 29 | 89.7 | 1 | 32 | 93.5 | 1 | 649 | 124.5 | 2 | 69 | 105.3
Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 2 | 709 | 72.0 | 2 | 146 | 63.0 | 2 | 20 | 61.9 | 2 | 29 | 84.7 | 2 | 367 | 70.4 | 1 | 75 | 114.5
Sudden infant death syndrome(R95) | 4 | 252 | 25.6 | 5 | 45 | 19.4 | … | * | * | 4 | 10 | 29.2 | 4 | 119 | 22.8 | 3 | 36 | 54.9
Accidents (unintentional injuries)(V01–X59) | 5 | 186 | 18.9 | 6 | 24 | 10.4 | … | * | * | … | * | * | 5 | 107 | 20.5 | 5 | 23 | 35.1
Newborn affected by maternal complications of pregnancy(P01) | 3 | 331 | 33.6 | 3 | 61 | 26.3 | … | * | * | 3 | 15 | 43.8 | 3 | 179 | 34.3 | 4 | 31 | 47.3

… Category not applicable.

* Estimate does not meet National Center for Health Statistics standards of reliability.

^1^For infants born to Asian non-Hispanic women, Bacterial sepsis (P36.9) was the fourth leading cause of death, with 35 deaths and a rate of 15.4. Complications of placenta, cord and membranes (P02) was the fifth leading cause of death, with 30 deaths and a rate of 13.2

^2^For infants born to Central and South American women, Bacterial sepsis (P36.9) was the fourth leading cause of death, with 49 deaths and a rate of 21.1.

NOTES: Certain cause-specific infant mortality rates and rankings cannot be shown for infants of Native Hawaiian or Other Pacific Islander non-Hispanic, Cuban, and Dominican women because of the small number of infant deaths. Race and Hispanic origin are reported separately on birth certificates. Race categories are consistent with the 1997 Office of Management and Budget standards. People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Infant mortality by state

- Infant mortality ranged from a low of 2.97 infant deaths per 1,000 births in New Hampshire to a high of 9.65 in Mississippi (Figure 4, Table 5).
- Ten states had infant mortality rates significantly lower than the U.S. infant mortality rate: California, Colorado, Connecticut, Iowa, Massachusetts, Minnesota, New Hampshire, New Jersey, New York, and Washington.
- Sixteen states had infant mortality rates significantly higher than the U.S. infant mortality rate: Alabama, Arkansas, Delaware, Georgia, Indiana, Louisiana, Michigan, Mississippi, Missouri, Nebraska, North Carolina, Ohio, Oklahoma, South Carolina, South Dakota, and Tennessee.

Figure 4 Infant mortality rate, by state: United States, 2024

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 4 is a U.S. map showing infant mortality rates by state for 2024.

Table 5 Infant mortality rate: United States and each State, 2024

[By place of residence]

Area | Rate(deaths per 1,000 births) | Infant deaths | Live births
United States^1^ | 5.52 | 20,048 | 3,628,934
Alabama | 7.06 | 409 | 57,934
Alaska | 6.82 | 61 | 8,943
Arizona | 5.40 | 425 | 78,711
Arkansas | 8.28 | 293 | 35,395
California | 4.18 | 1,682 | 402,075
Colorado | 4.54 | 292 | 64,268
Connecticut | 4.51 | 156 | 34,599
Delaware | 7.77 | 82 | 10,550
District of Columbia | 6.04 | 46 | 7,616
Florida | 5.74 | 1,287 | 224,389
Georgia | 6.40 | 809 | 126,437
Hawaii | 4.36 | 65 | 14,917
Idaho | 4.73 | 110 | 23,276
Illinois | 5.73 | 720 | 125,731
Indiana | 6.33 | 508 | 80,257
Iowa | 4.50 | 164 | 36,436
Kansas | 5.86 | 199 | 33,984
Kentucky | 5.88 | 311 | 52,913
Louisiana | 7.58 | 404 | 53,305
Maine | 4.48 | 52 | 11,601
Maryland | 5.53 | 364 | 65,797
Massachusetts | 3.49 | 238 | 68,184
Michigan | 6.33 | 630 | 99,525
Minnesota | 4.60 | 286 | 62,110
Mississippi | 9.65 | 323 | 33,473
Missouri | 6.44 | 438 | 67,998
Montana | 6.18 | 70 | 11,331
Nebraska | 6.54 | 162 | 24,785
Nevada | 5.34 | 173 | 32,381
New Hampshire | 2.97 | 35 | 11,770
New Jersey | 3.37 | 342 | 101,372
New Mexico | 5.16 | 110 | 21,328
New York | 3.95 | 811 | 205,489
North Carolina | 6.24 | 767 | 122,856
North Dakota | 5.92 | 57 | 9,634
Ohio | 6.65 | 843 | 126,795
Oklahoma | 7.42 | 356 | 47,962
Oregon | 4.93 | 192 | 38,963
Pennsylvania | 5.68 | 723 | 127,299
Rhode Island | 4.20 | 42 | 10,009
South Carolina | 7.49 | 440 | 58,768
South Dakota | 7.34 | 84 | 11,451
Tennessee | 6.41 | 537 | 83,833
Texas | 5.70 | 2,226 | 390,828
Utah | 5.16 | 241 | 46,664
Vermont | 5.57 | 28 | 5,023
Virginia | 5.95 | 560 | 94,054
Washington | 4.79 | 398 | 83,118
West Virginia | 6.64 | 113 | 17,022
Wisconsin | 5.91 | 353 | 59,686
Wyoming | 4.60 | 28 | 6,089
Puerto Rico | 7.50 | 136 | 18,128
Guam | 11.11 | 26 | 2,340

^1^Does not include Puerto Rico or Guam.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

## Acknowledgments

This report was prepared by the Division of Vital Statistics (DVS) under the general direction of DVS Director Paul Sutton; Robert Anderson, Chief, Statistical Analysis and Surveillance Branch; and Joyce Martin, Team Leader, Perinatal Research and Statistics Team, Statistical Analysis and Surveillance Branch. Rajesh Virkar, Chief of the Information Technology Branch (ITB), Annie S. Liu, and Prameela Sathunuru of ITB provided computer programming support. Annie S. Liu prepared the natality file. Annie S. Liu and Prameela Sathunuru prepared the linked birth/infant death data file. The Data Acquisition, Classification, and Evaluation Branch staff of DVS evaluated the quality of and acceptance procedures for the state data files on which this report is based. The National Center for Health Statistics Office of Information Services, Information Design and Publishing Staff, edited and produced this report: editor Jen Hurlburt and typesetter and graphic designer Jiale Feng.

## Technical Notes

### Data source and 2003 revision

Information on the data source for the linked birth/infant death file is available elsewhere (1). Additionally, further information on the 2003 revision of the birth certificate is available (3); see also the U.S. Standard Certificate of Live Birth (9).

### Weighting

In 2024, a record weight was added to the U.S. linked file to compensate for the 1.2% of infant death records that could not be linked to their corresponding birth certificates. The percentage of records linked varied by registration area, ranging from 95.3% to 100.0% (1). The number of infant deaths in the linked file for the 50 states and the District of Columbia was weighted to equal the sum of the linked plus unlinked infant deaths by state of occurrence of birth and age at death (younger than 7 days, 7–27 days, and 28–364 days). The addition of the weight reduced the potential for bias in comparing infant mortality rates by maternal and infant characteristics.

The 2024 linked file initially included 20,086 infant death records. Of these records, 19,836 were linked; 250 were unlinked because corresponding birth certificates could not be identified. The 20,086 linked and unlinked records contained 32 records of infants whose mothers’ usual place of residence was outside of the United States; these records were excluded from linked file analyses for a weighted total of 20,048 infant deaths by place of residence for 2024.

### Comparison of infant mortality data between linked file and vital statistics mortality file

The overall infant mortality rate of 5.52 from the 2024 period linked file is statistically the same as that from the 2024 vital statistics mortality file (5.53) (10). The number of infant deaths in the linked file (19,836) differs slightly from the number in the mortality file (20,050) (10). Differences in numbers of infant deaths between the two data sources are primarily due to geographic coverage differences. For the vital statistics mortality file, all deaths occurring in the 50 states and the District of Columbia are included regardless of the place of birth of the infant. In contrast, to be included in the U.S. linked file, both the birth and death must occur in the 50 states or the District of Columbia (the territory linked file is a separate file). Weighting of the linked file also may contribute to small differences in numbers and rates by specific variables between these two data sets.

### Period of gestation

Beginning with the 2014 data year, the National Center for Health Statistics (NCHS) transitioned to a new standard for estimating the gestational age of the newborn. The new measure—the obstetric estimate of gestation at delivery—replaces the measure based on the date of the last normal menses (11). Accordingly, gestational age data shown in this report are based on the obstetric estimate of gestation at delivery. National data based on obstetric estimate of gestation at delivery data are available only from data year 2007 forward. Information on and discussion of the reasons for the change, as well as a detailed comparison of the two measures, are presented elsewhere (11).

### Sex, birthweight, plurality, and nativity

Detailed definitions and more information on sex, birthweight, plurality, and nativity are available elsewhere (1,3).

### Cause-of-death classification

The mortality statistics presented in this report were compiled in accordance with the current revision of the International Statistical Classification of Diseases (ICD). ICD provides the basic guidance to code and classify causes of death, details disease classification, and supplies definitions, tabulation lists, the format of the death certificate, and the rules for coding cause of death. Cause-of-death data presented in this report were coded by procedures outlined in annual issues of the NCHS Instruction Manual (12,13).

In this report, tabulations of cause-of-death statistics are based solely on the underlying cause of death. Generally, more medical information is reported on death certificates than is directly reflected in the underlying cause of death. This is captured in NCHS multiple cause-of-death statistics (14,15).

### Tabulation lists and cause-of-death ranking

The cause-of-death rankings for ICD–10 are based on the “List of 130 Selected Causes of Infant Death.” The tabulation lists and rules for ranking leading causes of death are published in the NCHS Instruction Manual, Part 9: “ICD–10 Cause-of-death Lists for Tabulating Mortality Statistics” (16).

### Computation of rates

Information on and discussion of computation of rates (1) is also available from the “User Guide to the 2010 Natality Public Use File” at: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2010.pdf.

### Presentation of counts, rates, and percentages

An asterisk (*) in the tables indicates that a count, rate, or percentage does not meet NCHS standards of reliability (17,18). Three separate criteria are used to determine if a count (number of events), rate, or proportion meets these suppression standards (3).

#### Presentation of counts and rates

New criteria for showing counts and rates were adopted by NCHS beginning with 2023 data (17). For counts, the number of deaths is shown depending on the count of deaths and on the relative width of the confidence interval of the count, based on a gamma distribution. Before the 2023 data year, the number of deaths was shown regardless of the count. For rates, if a rate is shown depends on the count for the numerator and on the relative width of the confidence interval of the rate based on a Student’s t confidence interval for the logarithm of the rate. Rates published for data years before 2023 were represented by an asterisk when the numerator was fewer than 20 deaths. For detailed information on the new criteria, see “National Center for Health Statistics Data Presentation Standards for Rates and Counts” (17).

#### Presentation of percentages

For proportions (or percentages) for linked birth/infant deaths, new criteria adopted by NCHS were implemented starting with the 2023 data year (18). For 2023 and later, a proportion (percentage) was shown based on the denominator size and on the absolute or relative widths of the confidence interval of the proportion or percentage calculated using the Clopper–Pearson method. For the presentation criterion used before the 2023 data year, see the 2023 Natality User Guide (3). Starting in 2023, proportions or percentages based on fewer than 10 infant deaths are represented with an asterisk. For detailed information on these criteria, see “National Center for Health Statistics Data Presentation Standards for Proportions” (18).

### Random variation in infant mortality rates

For information and discussion on random variation and significance testing for linked data (1), see also the “User Guide to the 2010 Natality Public Use File” at: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2010.pdf.

### Availability of linked file

Linked file data are available for download from the Vital Statistics Online Data Portal: https://www.cdc.gov/nchs/data_access/vitalstatsonline.htm. Linked period file data may also be accessed via the Centers for Disease Control and Prevention’s WONDER database, available from: https://wonder.cdc.gov/lbd.html. Beginning with 2005, the public-use file no longer includes geographic detail; such files are available upon special request (see the NCHS Division of Vital Statistics data release policy at: https://www.cdc.gov/nchs/nvss/nvss-restricted-data.htm). Data are also available in issues of Vital and Health Statistics, Series 20; National Vital Statistics Reports; and NCHS Data Briefs from the NCHS website: https://www.cdc.gov/nchs/products/index.htm.

## References

1 National Center for Health Statistics. User guide to the 2024 period/2023 cohort linked birth/infant death public use file. 2026. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/period-cohort-linked/24PE23CO_linkedUG.pdf.
2 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2024. Natl Vital Stat Rep. 2026 Jun;75(2):1–48. DOI: 10.15620/cdc:252440.
3 National Center for Health Statistics. User guide to the 2024 natality public use file. 2025. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2024.pdf.
4 Ely DM, Driscoll AK. Infant mortality in the United States, 2017: Data from the period linked birth/infant death file. Natl Vital Stat Rep. 2019 Aug;68(10):1–20. PMID:3250120532501205.
5 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist 62(210):58782–90. 1997.
6 National Center for Health Statistics. 2003 revisions of the U.S. Standard Certificates and Reports. 2003. Available from: https://www.cdc.gov/nchs/nvss/vital_certificate_revisions.htm.
7 World Health Organization. International statistical classification of diseases and related health problems, 10th Revision. Volume 2, Instruction manual. 2010 ed. Geneva: World Health Organization; 2010.
8 Kochanek KD, Murphy SL, Xu J, Arias E. Deaths: Final data for 2017. Natl Vital Stat Rep. 2019 Jun;68(9):1–77. PMID:3250119932501199.
9 National Center for Health Statistics. U.S. Standard Certificate of Live Birth. 2003. Available from: https://www.cdc.gov/nchs/data/dvs/birth11-03final-ACC.pdf.
10 National Center for Health Statistics. Vital statistics online data portal. Mortality data files. Available from: https://www.cdc.gov/nchs/data_access/VitalStatsOnline.htm.
11 Martin JA, Osterman MJ, Kirmeyer SE, Gregory EC. Measuring gestational age in vital statistics data: Transitioning to the obstetric estimate. Natl Vital Stat Rep. 2015 Jun;64(5):1–20. PMID:2604708926047089.
12 National Center for Health Statistics. Instructions for classifying the underlying cause of death, 2025. NCHS Instruction Manual, part 2a. 2025.
13 National Center for Health Statistics. Vital statistics ICD–10 ACME decision tables for classifying underlying causes of death, 2024. NCHS Instruction Manual, part 2c. 2024.
14 National Center for Health Statistics. Mortality multiple cause-of-death public use data file documentation (published annually). 2024.
15 World Health Organization. Manual of the International Statistical Classification of Diseases, Injuries and Causes of Death: Based on the recommendations of the Ninth Revision Conference, 1975, and adopted by the Twenty-ninth World Health Assembly, 1975 revision. Geneva, Switzerland. 1977.
16 National Center for Health Statistics. ICD–10 cause-of-death lists for tabulating mortality statistics. Updated October 2020. NCHS Instruction Manual, part 9. 2020.
17 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D,et al. National Center for Health Statistics data presentation standards for rates and counts. Vital Health Stat 2. 2023 Mar;(200):1–26. DOI:10.15620/cdc:124368.
18 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. Vital Health Stat 2. 2017 Aug;(175):1–22.PMID:30248016.30248016

National Center for Health Statistics

Carolyn M. Greene, M.D., Acting Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science