# 75 Number 2 Births: Final Data for 2024

### Objectives

This report presents 2024 data on U.S. births by selected characteristics. Trends in fertility patterns and maternal and infant characteristics are described.

### Methods

Descriptive tabulations based on birth certificates of the 3.63 million births registered in 2024 are shown for various maternal demographic and health characteristics; medical and healthcare utilization, including source of payment for the delivery; and infant health characteristics. Selected data by mother’s state of residence and birth rates also are shown. Trends for 2010 to 2024 are presented for selected items and by race and Hispanic origin for 2016–2024.

### Results

A total of 3,628,934 births occurred in the United States in 2024, an increase of 1% from the record low reported for 2023. The general fertility rate declined 1% from 2023 to 53.8 births per 1,000 females ages 15–44 in 2024. Birth rates declined for females ages 15–34 from 2023 to 2024, rose for women ages 40–44, and were unchanged for females ages 10–14 and women ages 35–39 and 45–49. The total fertility rate declined 1% to 1,599.5 births per 1,000 women in 2024, a record low. Birth rates declined for both unmarried and married women from 2023 to 2024. Prenatal care beginning in the first trimester declined to 75.5% in 2024. The percentage of women who smoked during pregnancy declined to 2.4%. The cesarean delivery rate increased by less than 1% to 32.4%. Private insurance as the source of payment for the delivery increased to 51.8% of births, while Medicaid deliveries declined to 40.2%. The preterm birth rate (10.41%) was unchanged from 2023; low birthweight births declined 1% (8.52%). The twin birth rate declined 2% in 2024 to 30.1 per 1,000 births; the triplet and higher-order multiple birth rate was 71.3 per 100,000 births compared with 73.8 for 2023.

## Introduction

This report presents detailed data on numbers and characteristics of births in 2024; birth and fertility rates; maternal demographic and health characteristics; medical and healthcare utilization, including source of payment for the delivery; and infant health characteristics. A report on provisional birth statistics for 2024 that presented data on selected topics is based on nearly all 2024 births (99.92%) (1); a National Center for Health Statistics Data Brief presented selected characteristics based on final data for 2024 births (2).

In addition to the tabulations included in this report, more detailed analysis is possible using the annual natality public-use file. The data file may be downloaded from: https://www.cdc.gov/nchs/data_access/Vitalstatsonline.htm (3). The public-use file does not include geographic detail, but a file with this information may be available by request (4). Birth data may also be accessed through CDC WONDER, the Centers for Disease Control and Prevention’s (CDC) user-friendly web-based data query system that makes several CDC information resources available to public health professionals and the public (5).

Detailed tables on selected topics are included in this report. Several additional topics previously included as supplemental tables (see “Births: Final Data for 2022” [6]) or in the Technical Notes (see “Births: Final Data for 2023” [7]) can be found in Tables A–D and in the “User Guide to the 2024 Natality Public Use File” (8). Such topics include births by attendant and place of delivery, mean age of mother by live-birth order, maternal prepregnancy body mass index, infections during pregnancy, and maternal morbidity. For information on data quality, see reports that assess the quality of selected medical and health data from the 2003 revised birth certificate and the 2024 User Guide (8–10).

Table A Selected demographic characteristics of births, by race and Hispanic origin of mother: United States, 2024

[Birth rates are births per 1,000 population. Fertility rates are computed by relating total births, regardless of age of mother, to females ages 15–44. Total fertility rates are sums of birth rates for 5-year age groups multiplied by 5. First-birth rates are computed by relating first births, regardless of age of mother, to females ages 15–44. Unmarried rates are births to unmarried females per 1,000 unmarried females ages 15–44. Populations are estimated as of July 1. Mean age at first birth is the arithmetic average of the age of mothers at the time of birth, computed directly from the frequency of first births by age of mother]

Characteristic | All races and origins^2^ | Non-Hispanic, single race^1^
Characteristic | All races and origins^2^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian and Other Pacific Islander | White | Hispanic^3^
| Number
Births | 3,628,934 | 24,021 | 226,860 | 473,377 | 10,375 | 1,783,156 | 984,092
| Rate
Birth rate | 10.7 | 10.0 | 10.6 | 11.1 | 15.9 | 9.2 | 14.5
Fertility rate | 53.8 | 46.8 | 46.3 | 50.9 | 72.4 | 51.5 | 64.3
Total fertility rate | 1,599.5 | 1,380.5 | 1,262.0 | 1,501.0 | 2,190.0 | 1,527.5 | 1,925.5
First birth rate^4^ | 21.3 | 15.6 | 21.9 | 18.3 | 21.0 | 20.7 | 24.5
Unmarried rate | 35.5 | 47.0 | 11.4 | 46.4 | 71.5 | 24.1 | 56.4
| Ratio
Sex ratio^5^ | 1,045 | 1,067 | 1,060 | 1,033 | 1,047 | 1,049 | 1,037
| Percent
Births to mothers younger than age 20 | 3.8 | 7.5 | 0.4 | 5.7 | 4.4 | 2.5 | 5.9
Births to mothers age 40 and older | 4.2 | 2.7 | 7.2 | 4.7 | 3.8 | 3.9 | 3.7
4th and higher-order births^5^ | 12.8 | 22.7 | 5.7 | 18.6 | 28.6 | 11.2 | 14.0
Births to unmarried mothers | 39.5 | 68.6 | 11.5 | 68.6 | 53.7 | 26.2 | 54.2
Mothers born in the 50 states or District of Columbia | 75.5 | 98.4 | 23.7 | 79.6 | 37.1 | 93.0 | 52.3
Educational attainment of mother:
High school diploma or higher | 88.6 | 82.1 | 95.4 | 88.5 | 79.3 | 93.8 | 77.8
Bachelor's degree or higher | 36.7 | 11.6 | 71.0 | 20.7 | 10.1 | 47.5 | 18.4
| Mean
Age of mother at first birth | 27.6 | 24.3 | 31.7 | 26.1 | 25.3 | 28.4 | 25.8

^1^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

^2^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^3^Includes all people of Hispanic origin of any race; see Technical Notes.

^4^Based on live-birth order.

^5^Male births per 1,000 female births.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality date file.

Table B Selected demographic characteristics of births, by Hispanic origin of mother: United States, 2024

[Mean age at first birth is the arithmetic average of the age of mothers at time of birth, computed directly from the frequency of first births by age of mother]

Characteristic | Total^1^ | Central and South American | Cuban | Dominican | Mexican | Puerto Rican | Other and unknown Hispanic
| Number
Births | 984,092 | 231,723 | 32,315 | 34,221 | 521,149 | 65,515 | 99,169
| Ratio
Sex ratio^2^ | 1,037 | 1,033 | 1,044 | 1,032 | 1,039 | 1,039 | 1,037
| Percent
Births to mothers younger than age 20 | 5.9 | 6.5 | 2.1 | 3.3 | 6.1 | 5.6 | 6.0
Births to mothers age 40 and older | 3.7 | 4.5 | 4.0 | 4.7 | 3.4 | 3.1 | 3.9
4th and higher-order births^3^ | 14.0 | 12.8 | 4.6 | 9.2 | 15.7 | 13.6 | 13.4
Mothers born in the 50 states or District of Columbia | 52.3 | 15.3 | 32.9 | 30.5 | 65.2 | 73.1 | 70.8
Educational attainment of mother:
High school diploma or higher | 77.8 | 62.0 | 89.5 | 87.4 | 80.8 | 88.5 | 84.1
Bachelor's degree or higher | 18.4 | 18.3 | 33.2 | 25.2 | 16.2 | 21.4 | 21.6
| Mean
Age of mother at first birth | 25.8 | 26.1 | 28.1 | 26.9 | 25.4 | 26.0 | 26.2

^1^Includes origin not stated.

^2^Male births per 1,000 female births.

^3^Based on live-birth order.

NOTES: People of Hispanic origin may be of any race. In this table, Hispanic women are classified only by place of origin; non-Hispanic women are not shown. Other and unknown Hispanic includes origins not otherwise classified, including Spaniard. See Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table C Selected medical and health characteristics of births, by race and Hispanic origin of mother: United States, 2024

Characteristic | All races and origins^2^ | Non-Hispanic, single race^1^ | | | | | Hispanic^3^
Characteristic | All races and origins^2^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian and Other Pacific Islander | White | Hispanic^3^
Mother | Percent
Prenatal care initiation:
First trimester | 75.5 | 64.0 | 80.8 | 65.1 | 47.6 | 82.1 | 67.8
Late or no care^4^ | 7.3 | 12.9 | 5.3 | 10.9 | 22.7 | 4.8 | 10.0
Quit smoking before pregnancy^5^ | 22.3 | 21.8 | 47.4 | 23.1 | 36.3 | 20.1 | 36.8
Smoked during pregnancy | 2.4 | 8.6 | 0.1 | 2.3 | 1.3 | 3.5 | 0.6
Pregnancy resulted from infertility treatment^6^ | 2.6 | 0.6 | 5.6 | 1.2 | 0.6 | 3.5 | 1.1
Mother received WIC^7^ food for herself duringthis pregnancy | 32.1 | 48.4 | 16.6 | 47.3 | 36.3 | 19.6 | 50.4
Diabetes:
Prepregnancy (diagnosis before this pregnancy) | 1.3 | 3.3 | 1.6 | 1.8 | 2.7 | 1.0 | 1.5
Gestational (diagnosis during this pregnancy) | 8.5 | 12.3 | 16.2 | 6.9 | 11.4 | 7.6 | 8.9
Overweight or obese (BMI^8^ of 25.0 or over) | 60.1 | 70.3 | 41.1 | 68.9 | 78.2 | 56.2 | 67.2
Induction of labor | 33.9 | 36.0 | 31.9 | 32.8 | 27.4 | 36.5 | 30.1
Certified nurse midwife delivery | 12.0 | 19.2 | 9.5 | 10.7 | 10.9 | 12.8 | 11.2
Home births | 1.6 | 0.9 | 0.4 | 0.8 | 0.7 | 2.5 | 0.6
Cesarean delivery (total) | 32.4 | 29.8 | 34.4 | 37.5 | 33.1 | 31.0 | 32.1
Low risk^9^ | 26.6 | 24.1 | 30.1 | 31.5 | 29.0 | 25.5 | 25.9
Source of payment for the delivery:
Medicaid | 40.2 | 63.2 | 21.3 | 62.4 | 58.3 | 26.6 | 57.3
Private | 51.8 | 24.6 | 72.8 | 32.0 | 28.6 | 65.9 | 32.3
Self-pay | 4.7 | 2.5 | 3.3 | 2.6 | 7.3 | 4.3 | 7.1
Other^10^ | 3.3 | 9.7 | 2.7 | 3.0 | 5.8 | 3.3 | 3.2
Infant was being breastfed at discharge^11^ | 85.0 | 76.5 | 89.7 | 76.0 | 77.6 | 86.3 | 87.1
Infant
Gestational age:
Preterm^12^ | 10.41 | 12.64 | 9.16 | 14.86 | 12.54 | 9.49 | 10.07
Early preterm^13^ | 2.72 | 3.39 | 2.30 | 4.85 | 3.47 | 2.26 | 2.56
Late preterm^14^ | 7.69 | 9.25 | 6.85 | 10.01 | 9.08 | 7.22 | 7.51
Birthweight^15^:
Very low birthweight^16^ | 1.33 | 1.44 | 1.20 | 2.83 | 1.62 | 0.99 | 1.23
Low birthweight^17^ | 8.52 | 9.03 | 9.55 | 15.01 | 9.49 | 6.97 | 7.85
Twin births^18^ | 30.1 | 26.1 | 23.3 | 42.0 | 24.5 | 31.3 | 23.4
Triplet and higher-order births^19^ | 71.3 | 83.3 | 51.6 | 110.3 | * | 75.7 | 49.3

^*^ Estimate does not meet National Center for Health Statistics standards of reliability.

^1^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

^2^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^3^Includes all people of Hispanic origin of any race; see Technical Notes.

^4^Late care is prenatal care beginning in the third trimester.

^5^Quit in the 3 months before pregnancy; based on births to women not reporting smoking during pregnancy per 100 women who smoked in the 3 months before pregnancy. See Technical Notes.

^6^Excludes data for Georgia and North Carolina; see User Guide in reference 8 in this report..

^7^Special Supplemental Nutrition Program for Women, Infants, and Children.

^8^Body mass index.

^9^Rate is the number of singleton, term (37 weeks of gestation or more based on the obstetric estimate), cephalic (head first), cesarean deliveries to women having a first birth per 100 women delivering singleton, term, cephalic births.

^10^Includes Indian Health Service, CHAMPUS or TRICARE, other government (federal, state, or local), or charity.

^11^Excludes data for California, which did not report if infant was being breastfed at discharge.

^12^Born before 37 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

^13^Born before 34 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

^14^Born between 34 and 36 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

^15^Equivalents of gram weights in pounds are shown in the User Guide; see reference 8 in this report.

^16^Less than 1,500 grams (3 lb 4 oz).

^17^Less than 2,500 grams (5 lb 8 oz).

^18^Live births in twin deliveries per 1,000 live births.

^19^Live births in triplet and other higher-order multiple deliveries per 100,000 live births.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table D Selected medical and health characteristics of births, by Hispanic origin of mother: United States, 2024

Characteristic | Total | Central and South American | Cuban | Dominican | Mexican | Puerto Rican | Other and unknown Hispanic
Mother | Percent
Prenatal care initiation:
First trimester | 67.8 | 57.8 | 69.4 | 71.6 | 70.1 | 74.8 | 72.4
Late or no care^1^ | 10.0 | 14.1 | 9.9 | 8.9 | 9.2 | 6.6 | 7.8
Quit smoking before pregnancy^2^ | 36.8 | 52.6 | 37.1 | 44.2 | 38.4 | 28.8 | 32.0
Smoked during pregnancy | 0.6 | 0.2 | 0.8 | 0.3 | 0.6 | 2.3 | 0.9
Pregnancy resulted from infertilitytreatment^3^ | 1.1 | 0.9 | 1.4 | 1.7 | 0.9 | 1.7 | 1.4
Mother received WIC^4^ food for herselfduring this pregnancy | 50.4 | 53.6 | 48.8 | 54.4 | 49.9 | 45.8 | 48.2
Diabetes:
Prepregnancy (diagnosis before this pregnancy) | 1.5 | 1.1 | 0.9 | 1.3 | 1.6 | 1.7 | 1.4
Gestational (diagnosis during this pregnancy) | 8.9 | 7.5 | 7.7 | 8.4 | 9.7 | 8.9 | 8.7
Overweight or obese (BMI^5^of25.0 or over) | 67.2 | 63.0 | 57.6 | 66.1 | 69.9 | 66.2 | 66.5
Induction of labor | 30.1 | 28.2 | 27.6 | 30.8 | 30.4 | 34.2 | 31.7
Certified nurse midwife delivery | 11.2 | 12.4 | 7.4 | 11.4 | 10.5 | 15.3 | 10.9
Home births | 0.6 | 0.5 | 0.7 | 0.5 | 0.5 | 1.0 | 0.8
Cesarean delivery (total) | 32.1 | 31.0 | 43.4 | 41.5 | 31.1 | 33.4 | 32.8
Low risk^6^ | 25.9 | 24.5 | 36.1 | 29.7 | 25.1 | 27.8 | 26.3
Source of payment for the delivery:
Medicaid | 57.3 | 59.4 | 52.9 | 62.5 | 57.2 | 54.3 | 54.8
Private | 32.3 | 25.8 | 43.1 | 30.8 | 32.9 | 39.4 | 37.2
Self-pay | 7.1 | 11.6 | 2.3 | 3.4 | 6.8 | 1.7 | 4.3
Other^7^ | 3.2 | 3.2 | 1.7 | 3.2 | 3.1 | 4.6 | 3.7
Infant was being breastfed at discharge^8^ | 87.1 | 88.5 | 90.6 | 89.0 | 86.6 | 84.2 | 86.2
Infant
Gestational age:
Preterm^9^ | 10.07 | 9.51 | 9.60 | 10.40 | 10.00 | 11.58 | 10.78
Early preterm^10^ | 2.56 | 2.34 | 2.63 | 2.90 | 2.52 | 3.10 | 2.82
Late preterm^11^ | 7.51 | 7.17 | 6.98 | 7.50 | 7.48 | 8.48 | 7.96
Birthweight^12^:
Very low birthweight^13^ | 1.23 | 1.13 | 1.25 | 1.53 | 1.19 | 1.54 | 1.33
Low birthweight^14^ | 7.85 | 7.27 | 7.26 | 8.89 | 7.64 | 10.12 | 8.62
Twin births^15^ | 23.45 | 19.99 | 26.30 | 30.30 | 23.04 | 31.14 | 25.29
Triplet and higher-order births^16^ | 49.28 | 23.30 | 80.46 | 75.98 | 47.40 | 90.06 | 73.61

^1^Late care is prenatal care beginning in the third trimester.

^2^Quit in the 3 months before pregnancy; based on births to women not reporting smoking during pregnancy per 100 women who smoked in the 3 months before pregnancy.

^3^Excludes data for Georgia and North Carolina; see User Guide in reference 8 in this report..

^4^Special Supplemental Nutrition Program for Women, Infants, and Children.

^5^Body mass index.

^6^Rate is number of singleton, term (37 weeks of gestation or more based on the obstetric estimate), cephalic (head first), cesarean deliveries to women having a first birth per 100 women delivering singleton, term, cephalic births.

^7^Includes Indian Health Service, CHAMPUS or TRICARE, other government (federal, state, or local), or charity.

^8^Excludes data for California, which did not report if infant was being breastfed at discharge.

^9^Born before 37 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

^10^Born before 34 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

^11^Born between 34 and 36 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

^12^Equivalents of gram weights in pounds are shown in the User Guide; see reference 8 in this report.

^13^Less than 1,500 grams (3 lb 4 oz).

^14^Less than 2,500 grams (5 lb 8 oz).

^15^Live births in twin deliveries per 1,000 live births.

^16^Live births in triplet and other higher-order multiple deliveries per 100,000 live births.

NOTES: People of Hispanic origin may be of any race. In this table, Hispanic women are classified only by place of origin; non-Hispanic women are not shown. Other and unknown Hispanic includes origins not otherwise classified, including Spaniard. See Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

## Methods

Data shown in this report are based on 100% of the birth certificates registered in all states and the District of Columbia (D.C.) to U.S. residents. More than 99% of births occurring in the United States are registered (8). Tables showing data by state also provide separate information for Puerto Rico, Guam, U.S. Virgin Islands, American Samoa, and Northern Mariana Islands (Northern Marianas). These areas, however, are not included in totals for the United States.

The 2024 User Guide provides information on levels of incomplete reporting by state and measurement of data items included in this report (such as marital status, cigarette smoking before and during pregnancy, use and timing of prenatal care, source of payment for the delivery, method of delivery, gestational age, birthweight, plurality, and additional items in Tables A–D not otherwise discussed), as well as imputation techniques used, computation of derived statistics, population denominators, standards of reliability, significance testing, and definition of terms (8).

In this report, data for 2016–2024 are based on the 2003 revision of the U.S. Standard Certificate of Live Birth (11); data for 2010–2015 are based on both the 1989 and 2003 birth certificate revisions. The 2003 revision is described in detail elsewhere (12). Longer-term trends previously shown in this report series can be found in earlier reports (see “Births: Final Data for 2015” [13]).

The race and Hispanic-origin groups shown in this report follow 1997 Office of Management and Budget standards and differ from the bridged-race categories shown in most previous reports that are based on data from 2015 and earlier (13,14). The categories are Hispanic; American Indian and Alaska Native; non-Hispanic single race (subsequently, American Indian and Alaska Native); Asian, non-Hispanic single race (subsequently, Asian); Black or African American, non-Hispanic single race (subsequently, Black); Native Hawaiian and Other Pacific Islander, non-Hispanic single race (subsequently, Native Hawaiian and Other Pacific Islander); and White, non-Hispanic single race (subsequently, White). Because single-race data are not available for the entire United States before 2016, race data for only 2016–2024 are shown. For more information on differences between single- and bridged-race groups, see “Births: Final Data for 2016” (15).

Race and Hispanic origin are reported independently on the birth certificate. Tables in this report show data for the categories Hispanic and all non-Hispanic race groups listed above. Data are also presented in some tables for specific Hispanic groups: Central and South American, Cuban, Dominican, Mexican, Puerto Rican, and other and unknown Hispanic, which includes Hispanic origins not categorized including Spaniard. Before 2018, data for the Dominican subgroup had been included in the category other and unknown Hispanic. American Samoa does not collect information on Hispanic origin.

In this report, the total number of births includes births to women up to age 64. In tables that include age of mother, the oldest age groups shown (40–54, 45–49, 45–54, or 50–54) include births to mothers up to age 64.

Birth and fertility rates for 2020 shown in this report have been revised and may differ from those published in “Births: Final Data for 2020” and elsewhere (16). Previously published birth and fertility rates for 2020 were based on postcensal population estimates derived from the 2010 census. The revised rates shown in this report are based on the blended base population estimates produced by the U.S. Census Bureau instead of the April 1, 2020, decennial population counts (Technical Notes).

## Demographic Characteristics

### Births and birth rates

#### Number of births

In 2024, 3,628,934 births were registered in the United States, up 1% from the record low reported for 2023 (3,596,017). The number of births declined 2% from 2022 to 2023, were essentially unchanged from 2021 to 2022, increased 1% from 2020 to 2021, and declined 4% from 2019 to 2020 and 6% from 2014 to 2019 (Table 1, Figure 1) (13).

Table 1 Births and birth rates: United States, 2010–2024, and by race and Hispanic origin of mother: United States, 2016–2024

[Birth rates are births per 1,000 population in specified group. Fertility rates are births per 1,000 females ages 15–44 in specified group. Populations based on counts enumerated as of April 1 for 2010 and estimated as of April 1 for 2020 and July 1 for all other years]

Race and Hispanic origin and year | Number of births | Birth rate | Fertility rate
All races and origins^1^
2024 | 3,628,934 | 10.7 | 53.8
2023 | 3,596,017 | 10.7 | 54.5
2022 | 3,667,758 | 11.0 | 56.0
2021 | 3,664,292 | 11.0 | 56.3
2020 | 3,613,647 | 10.9 | 55.7
2019 | 3,747,540 | 11.4 | 58.3
2018 | 3,791,712 | 11.6 | 59.1
2017 | 3,855,500 | 11.8 | 60.3
2016 | 3,945,875 | 12.2 | 62.0
2015 | 3,978,497 | 12.4 | 62.5
2014 | 3,988,076 | 12.5 | 62.9
2013 | 3,932,181 | 12.4 | 62.5
2012 | 3,952,841 | 12.6 | 63.0
2011 | 3,953,590 | 12.7 | 63.2
2010 | 3,999,386 | 13.0 | 64.1
Non-Hispanic, single race^2^
American Indian and Alaska Native:
2024 | 24,021 | 10.0 | 46.8
2023 | 24,571 | 10.3 | 48.0
2022 | 25,721 | 10.8 | 50.6
2021 | 26,124 | 10.8 | 50.8
2020 | 26,813 | 11.1 | 52.6
2019 | 28,450 | 11.9 | 56.2
2018 | 29,092 | 12.2 | 57.7
2017 | 29,957 | 12.6 | 59.5
2016 | 31,452 | 13.3 | 62.7
Asian:
2024 | 226,860 | 10.6 | 46.3
2023 | 215,738 | 10.7 | 47.8
2022 | 218,994 | 11.1 | 49.4
2021 | 213,813 | 11.2 | 49.6
2020 | 219,068 | 11.6 | 50.4
2019 | 238,769 | 13.0 | 55.3
2018 | 240,798 | 13.2 | 55.6
2017 | 249,250 | 13.8 | 58.0
2016 | 254,471 | 14.6 | 61.1
Black:
2024 | 473,377 | 11.1 | 50.9
2023 | 491,494 | 11.7 | 53.7
2022 | 511,439 | 12.3 | 56.1
2021 | 517,889 | 12.5 | 57.4
2020 | 529,811 | 12.8 | 58.9
2019 | 548,075 | 13.4 | 61.4
2018 | 552,029 | 13.6 | 62.0
2017 | 560,715 | 13.9 | 63.1
2016 | 558,622 | 14.0 | 63.3
Native Hawaiian and Other Pacific Islander:
2024 | 10,375 | 15.9 | 72.4
2023 | 10,115 | 16.1 | 73.2
2022 | 10,122 | 16.5 | 74.8
2021 | 9,531 | 15.8 | 71.5
2020 | 9,626 | 16.1 | 72.5
2019 | 9,770 | 17.0 | 74.9
2018 | 9,476 | 16.6 | 73.0
2017 | 9,426 | 16.7 | 72.8
2016 | 9,342 | 16.8 | 72.9
White:
2024 | 1,783,156 | 9.2 | 51.5
2023 | 1,787,051 | 9.3 | 51.7
2022 | 1,840,739 | 9.5 | 53.1
2021 | 1,887,656 | 9.7 | 54.4
2020 | 1,843,432 | 9.4 | 53.0
2019 | 1,915,912 | 9.8 | 55.3
2018 | 1,956,413 | 10.0 | 56.3
2017 | 1,992,461 | 10.2 | 57.2
2016 | 2,056,332 | 10.5 | 58.8
Hispanic^3^
2024 | 984,092 | 14.5 | 64.3
2023 | 945,200 | 14.5 | 64.7
2022 | 937,421 | 14.7 | 65.7
2021 | 885,916 | 14.1 | 63.4
2020 | 866,713 | 14.0 | 62.9
2019 | 886,467 | 14.6 | 65.3
2018 | 886,210 | 14.8 | 65.9
2017 | 898,764 | 15.2 | 67.6
2016 | 918,447 | 16.0 | 70.6

^1^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^2^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

^3^Includes all people of Hispanic origin of any race; see Technical Notes.

NOTE: Rates for 2020 have been revised and may differ from those published in ‘‘Births: Final Data for 2020”; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 1 Live births and general fertility rate: United States, 1970-2024

NOTE: Rate for 2020 has been revised and differs from that published in Births: Final Data for 2020.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 1 is a line graph showing the number of live births and the general fertility rate from 1970 through 2024.

Among race and Hispanic-origin groups, the number of births declined 4% for Black, 2% for American Indian and Alaska Native, and less than 1% for White women from 2023 to 2024, and rose 4% for Hispanic and 5% for Asian women (Tables A, 1, 3, and 5). The change in the number of births for Native Hawaiian and Other Pacific Islander women was not significant. Among specified Hispanic groups, births rose 2% for Dominican, 3% for Mexican, 8% for Cuban, and 11% for Central and South American women (Table B; see also Tables 3 and 5 in the 2024 User Guide [8]) (7). The change in the number of births for Puerto Rican women was not significant.

Table 5 Births, by race and Hispanic origin of mother: United States, each state and territory, 2024

[By place of] residence

Area | All races and origins^2^ | Non-Hispanic, single race^1^ | | | | | Hispanic^3^
Area | All races and origins^2^ | American Indian or Alaska Native | Asian | Black | Native Hawaiian and Other Pacific Islander | White | Hispanic^3^
United States^4^ | 3,628,934 | 24,021 | 226,860 | 473,377 | 10,375 | 1,783,156 | 984,092
Alabama | 57,934 | 127 | 955 | 14,706 | 78 | 33,213 | 7,701
Alaska | 8,943 | 1,531 | 468 | 208 | 311 | 4,477 | 791
Arizona | 78,711 | 3,199 | 2,805 | 4,427 | 230 | 29,340 | 36,108
Arkansas | 35,395 | 183 | 877 | 5,725 | 521 | 22,511 | 4,664
California | 402,075 | 1,185 | 58,695 | 17,722 | 1,416 | 102,406 | 196,312
Colorado | 64,268 | 309 | 2,677 | 2,929 | 256 | 34,331 | 21,243
Connecticut | 34,599 | 31 | 1,909 | 3,944 | * | 17,857 | 10,062
Delaware | 10,550 | 18 | 599 | 2,711 | * | 4,626 | 2,212
District of Columbia | 7,616 | 13 | 373 | 3,188 | * | 2,415 | 1,399
Florida | 224,389 | 222 | 7,112 | 42,908 | 155 | 90,531 | 79,481
Georgia | 126,437 | 113 | 6,023 | 39,320 | 93 | 53,236 | 24,135
Hawaii | 14,917 | 23 | 3,540 | 301 | 1,431 | 2,818 | 2,697
Idaho | 23,276 | 207 | 408 | 319 | 67 | 17,215 | 4,427
Illinois | 125,731 | 88 | 8,897 | 17,272 | 36 | 64,630 | 31,861
Indiana | 80,257 | 61 | 2,659 | 10,082 | 58 | 53,994 | 11,438
Iowa | 36,436 | 135 | 986 | 2,707 | 386 | 26,771 | 4,667
Kansas | 33,984 | 149 | 1,011 | 2,099 | 110 | 22,535 | 7,051
Kentucky | 52,913 | 32 | 1,091 | 4,829 | 113 | 39,603 | 5,660
Louisiana | 53,305 | 267 | 1,046 | 18,386 | 27 | 26,427 | 6,291
Maine | 11,601 | 72 | 192 | 799 | * | 9,669 | 355
Maryland | 65,797 | 79 | 4,469 | 18,330 | 27 | 25,368 | 15,174
Massachusetts | 68,184 | 50 | 5,582 | 7,752 | 21 | 35,107 | 16,521
Michigan | 99,525 | 321 | 4,372 | 15,472 | 40 | 67,836 | 8,281
Minnesota | 62,110 | 716 | 4,660 | 7,310 | 85 | 40,026 | 7,235
Mississippi | 33,473 | 236 | 427 | 12,835 | 17 | 17,212 | 2,354
Missouri | 67,998 | 182 | 1,749 | 8,243 | 256 | 48,716 | 6,290
Montana | 11,331 | 914 | 121 | 66 | * | 9,056 | 783
Nebraska | 24,785 | 249 | 811 | 1,482 | 46 | 15,860 | 5,598
Nevada | 32,381 | 205 | 2,470 | 4,008 | 339 | 10,509 | 13,189
New Hampshire | 11,770 | 10 | 445 | 260 | * | 9,958 | 875
New Jersey | 101,372 | 48 | 10,416 | 11,436 | 33 | 45,574 | 31,099
New Mexico | 21,328 | 2,097 | 403 | 362 | 19 | 5,311 | 12,640
New York | 205,489 | 316 | 20,759 | 25,564 | 50 | 101,902 | 51,898
North Carolina | 122,856 | 1,228 | 5,391 | 24,854 | 139 | 62,159 | 25,485
North Dakota | 9,634 | 616 | 248 | 556 | 41 | 6,779 | 842
Ohio | 126,795 | 70 | 3,968 | 19,693 | 123 | 87,830 | 10,761
Oklahoma | 47,962 | 4,046 | 1,314 | 3,374 | 248 | 25,060 | 9,335
Oregon | 38,963 | 350 | 2,041 | 1,134 | 398 | 22,810 | 9,370
Pennsylvania | 127,299 | 154 | 6,305 | 15,073 | 41 | 81,773 | 19,702
Rhode Island | 10,009 | 31 | 420 | 708 | * | 5,429 | 3,088
South Carolina | 58,768 | 122 | 1,275 | 14,387 | 79 | 32,336 | 8,893
South Dakota | 11,451 | 1,400 | 196 | 367 | 19 | 8,110 | 966
Tennessee | 83,833 | 101 | 2,070 | 13,004 | 84 | 53,217 | 13,501
Texas | 390,828 | 584 | 23,546 | 44,543 | 608 | 118,491 | 195,948
Utah | 46,664 | 322 | 1,232 | 649 | 818 | 31,644 | 10,321
Vermont | 5,023 | 10 | 108 | 140 | * | 4,460 | 203
Virginia | 94,054 | 117 | 7,123 | 17,318 | 131 | 49,182 | 17,296
Washington | 83,118 | 868 | 9,587 | 3,780 | 1,357 | 42,258 | 18,140
West Virginia | 17,022 | * | 175 | 586 | * | 15,212 | 577
Wisconsin | 59,686 | 450 | 2,789 | 5,467 | 27 | 40,779 | 8,243
Wyoming | 6,089 | 156 | 65 | 42 | * | 4,587 | 929
Puerto Rico | 18,128 | * | 32 | 49 | * | 412 | 17,627
Virgin Islands | 803 | * | 15 | 471 | * | 63 | 239
Guam | 2,340 | * | 571 | 23 | 1,446 | 128 | 32
American Samoa | 760 | --- | --- | --- | --- | --- | ---
Northern Marianas | 557 | * | 236 | * | 274 | * | *

^*^ Estimate does not meet National Center for Health Statistics standards of reliability.

--- Data not available.

^1^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

^2^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^3^Includes all people of Hispanic origin of any race; see Technical Notes.

^4^Excludes data for the territories.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 3 Births, by age of mother, live-birth order, and race and Hispanic origin of mother: United States, 2024

[Live-birth order is number of children born alive to mother]

Race and Hispanic origin of mother and live-birth order | All ages | Younger than 15 | 15–19 | | | | | | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49 | 50–54
Race and Hispanic origin of mother and live-birth order | All ages | Younger than 15 | Total | 15 | 16 | 17 | 18 | 19 | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49 | 50–54
All races and origins^1^
Total | 3,628,934 | 1,727 | 137,273 | 4,136 | 10,087 | 20,242 | 37,460 | 65,348 | 611,800 | 990,817 | 1,112,409 | 622,517 | 141,515 | 9,688 | 1,188
1st child | 1,427,020 | 1,698 | 118,128 | 4,019 | 9,564 | 18,475 | 32,699 | 53,371 | 354,230 | 404,955 | 362,002 | 151,974 | 30,846 | 2,768 | 419
2nd child | 1,137,499 | 21 | 16,703 | 100 | 457 | 1,601 | 4,226 | 10,319 | 182,473 | 323,629 | 368,841 | 203,639 | 39,415 | 2,473 | 305
3rd child | 586,733 | * | 1,768 | * | 22 | 91 | 372 | 1,277 | 55,760 | 162,543 | 207,742 | 129,524 | 27,701 | 1,520 | 174
4th child | 262,579 | * | 159 | * | * | 10 | 26 | 119 | 13,127 | 64,119 | 98,223 | 67,859 | 17,952 | 1,026 | 114
5th child | 107,130 | * | 21 | * | * | * | * | 16 | 2,863 | 21,199 | 40,115 | 32,123 | 10,069 | 659 | 81
6th child | 46,675 | * | * | * | * | * | * | * | 591 | 6,753 | 17,306 | 15,949 | 5,644 | 390 | 36
7th child | 21,984 | * | * | * | * | * | * | * | 128 | 2,306 | 7,752 | 8,319 | 3,246 | 214 | 19
8th child or higher order | 23,966 | * | * | * | * | * | * | * | 152 | 1,225 | 5,851 | 10,256 | 5,871 | 581 | 26
Not stated | 15,348 | * | 484 | 10 | 41 | 64 | 132 | 237 | 2,476 | 4,088 | 4,577 | 2,874 | 771 | 57 | 14
Non-Hispanic, single race^2^
American Indian and Alaska Native | 24,021 | 30 | 1,769 | 65 | 145 | 268 | 502 | 789 | 6,029 | 6,807 | 5,776 | 2,967 | 613 | 28 | *
1st child | 7,922 | 30 | 1,507 | 65 | 137 | 250 | 432 | 623 | 3,088 | 1,917 | 919 | 390 | 64 | * | *
2nd child | 6,173 | * | 222 | * | * | 16 | 59 | 141 | 1,864 | 2,050 | 1,382 | 543 | 104 | * | *
3rd child | 4,346 | * | 25 | * | * | * | * | 18 | 746 | 1,513 | 1,361 | 599 | 96 | * | *
4th child | 2,598 | * | * | * | * | * | * | * | 219 | 797 | 966 | 504 | 105 | * | *
5th child | 1,333 | * | * | * | * | * | * | * | 55 | 313 | 523 | 356 | 84 | * | *
6th child | 731 | * | * | * | * | * | * | * | 10 | 121 | 307 | 231 | 61 | * | *
7th child | 356 | * | * | * | * | * | * | * | * | 38 | 142 | 136 | 36 | * | *
8th child or higher order | 387 | * | * | * | * | * | * | * | * | 13 | 126 | 186 | 59 | * | *
Not stated | 175 | * | 12 | * | * | * | * | * | 42 | 45 | 50 | 22 | * | * | *
Asian | 226,860 | 11 | 888 | 26 | 53 | 101 | 236 | 472 | 9,126 | 41,742 | 93,782 | 64,989 | 14,998 | 1,147 | 177
1st child | 107,053 | 10 | 776 | 25 | 52 | 93 | 201 | 405 | 6,197 | 25,329 | 47,538 | 22,212 | 4,489 | 430 | 72
2nd child | 80,729 | * | 100 | * | * | * | 33 | 58 | 2,228 | 11,304 | 32,974 | 28,010 | 5,705 | 354 | 54
3rd child | 25,425 | * | * | * | * | * | * | * | 506 | 3,425 | 8,853 | 9,700 | 2,740 | 178 | 15
4th child | 8,158 | * | * | * | * | * | * | * | 124 | 1,065 | 2,683 | 3,063 | 1,119 | 88 | 15
5th child | 2,766 | * | * | * | * | * | * | * | 25 | 318 | 839 | 1,069 | 459 | 44 | 12
6th child | 1,107 | * | * | * | * | * | * | * | * | 109 | 355 | 392 | 221 | 25 | *
7th child | 412 | * | * | * | * | * | * | * | * | 20 | 103 | 169 | 111 | * | *
8th child or higher order | 387 | * | * | * | * | * | * | * | * | 19 | 108 | 149 | 93 | 13 | *
Not stated | 823 | * | * | * | * | * | * | * | 39 | 153 | 329 | 225 | 61 | * | *
Black | 473,377 | 464 | 26,450 | 984 | 2,186 | 4,275 | 7,114 | 11,891 | 96,149 | 124,237 | 128,145 | 75,600 | 20,422 | 1,624 | 286
1st child | 169,020 | 457 | 22,506 | 955 | 2,049 | 3,847 | 6,174 | 9,481 | 54,530 | 43,009 | 30,091 | 14,148 | 3,701 | 457 | 121
2nd child | 131,093 | * | 3,369 | 25 | 121 | 380 | 822 | 2,021 | 27,518 | 38,471 | 36,860 | 19,601 | 4,835 | 363 | 70
3rd child | 83,247 | * | 435 | * | * | 32 | 87 | 309 | 9,765 | 22,984 | 27,972 | 17,404 | 4,365 | 280 | 42
4th child | 45,050 | * | 42 | * | * | * | * | 34 | 2,889 | 11,380 | 16,420 | 11,025 | 3,080 | 192 | 22
5th child | 21,598 | * | * | * | * | * | * | * | 798 | 4,777 | 8,307 | 5,859 | 1,719 | 124 | 10
6th child | 10,465 | * | * | * | * | * | * | * | 179 | 1,886 | 4,108 | 3,194 | 1,018 | 74 | *
7th child | 5,238 | * | * | * | * | * | * | * | 44 | 728 | 2,074 | 1,719 | 631 | 39 | *
8th child or higher order | 5,405 | * | * | * | * | * | * | * | 30 | 399 | 1,692 | 2,236 | 955 | 83 | *
Not stated | 2,261 | * | 93 | * | * | 14 | 26 | 41 | 396 | 603 | 621 | 414 | 118 | 12 | *
Native Hawaiian and Pacific Islander | 10,375 | * | 453 | * | 25 | 54 | 128 | 238 | 2,467 | 3,055 | 2,607 | 1,391 | 376 | 20 | *
1st child | 2,984 | * | 375 | * | 25 | 50 | 110 | 182 | 1,183 | 744 | 479 | 159 | 36 | * | *
2nd child | 2,498 | * | 63 | * | * | * | 16 | 44 | 768 | 803 | 552 | 250 | 61 | * | *
3rd child | 1,890 | * | 11 | * | * | * | * | 10 | 339 | 710 | 521 | 246 | 63 | * | *
4th child | 1,273 | * | * | * | * | * | * | * | 139 | 433 | 409 | 246 | 40 | * | *
5th child | 770 | * | * | * | * | * | * | * | 23 | 204 | 312 | 175 | 51 | * | *
6th child | 453 | * | * | * | * | * | * | * | * | 98 | 174 | 142 | 31 | * | *
7th child | 250 | * | * | * | * | * | * | * | * | 30 | 84 | 93 | 40 | * | *
8th child or higher order | 213 | * | * | * | * | * | * | * | * | 16 | 64 | 78 | 52 | * | *
Not stated | 44 | * | * | * | * | * | * | * | * | 17 | 12 | * | * | * | *
White | 1,783,156 | 341 | 43,508 | 1,020 | 2,565 | 5,629 | 11,666 | 22,628 | 257,486 | 497,706 | 593,646 | 320,734 | 65,119 | 4,202 | 414
1st child | 714,195 | 332 | 37,955 | 1,000 | 2,467 | 5,209 | 10,358 | 18,921 | 151,700 | 219,168 | 205,164 | 82,761 | 15,723 | 1,252 | 140
2nd child | 585,809 | * | 4,863 | 17 | 79 | 379 | 1,172 | 3,216 | 76,504 | 163,622 | 208,039 | 111,849 | 19,625 | 1,181 | 118
3rd child | 277,791 | * | 484 | * | * | 17 | 95 | 367 | 22,128 | 73,599 | 103,945 | 65,137 | 11,872 | 558 | 67
4th child | 114,066 | * | 44 | * | * | * | * | 35 | 4,898 | 27,317 | 44,317 | 30,244 | 6,854 | 361 | 31
5th child | 43,377 | * | * | * | * | * | * | * | 972 | 8,485 | 16,771 | 13,218 | 3,667 | 229 | 31
6th child | 18,982 | * | * | * | * | * | * | * | 196 | 2,451 | 7,304 | 6,770 | 2,116 | 132 | 10
7th child | 9,512 | * | * | * | * | * | * | * | 39 | 778 | 3,318 | 3,902 | 1,388 | 80 | *
8th child or higher order | 12,331 | * | * | * | * | * | * | * | 62 | 400 | 2,493 | 5,455 | 3,532 | 381 | *
Not stated | 7,093 | * | 154 | * | 15 | 20 | 34 | 83 | 987 | 1,886 | 2,295 | 1,398 | 342 | 28 | *
Hispanic^3^
Total | 984,092 | 785 | 57,700 | 1,809 | 4,601 | 8,857 | 16,085 | 26,348 | 216,365 | 283,198 | 253,011 | 136,132 | 34,648 | 2,093 | 160
1st child | 374,363 | 773 | 49,432 | 1,752 | 4,348 | 8,062 | 13,899 | 21,371 | 123,722 | 101,640 | 66,078 | 26,674 | 5,518 | 472 | 54
2nd child | 294,189 | * | 7,294 | 48 | 229 | 729 | 1,950 | 4,338 | 66,520 | 96,788 | 78,429 | 37,009 | 7,678 | 424 | 40
3rd child | 174,471 | * | 707 | * | 10 | 33 | 161 | 499 | 19,990 | 54,419 | 58,711 | 32,618 | 7,604 | 398 | 24
4th child | 82,005 | * | 62 | * | * | * | 14 | 41 | 4,312 | 20,568 | 29,986 | 20,612 | 6,149 | 300 | 16
5th child | 33,079 | * | 11 | * | * | * | * | * | 856 | 6,151 | 11,824 | 10,324 | 3,693 | 208 | 12
6th child | 12,996 | * | * | * | * | * | * | * | 167 | 1,762 | 4,336 | 4,610 | 1,980 | 133 | *
7th child | 5,325 | * | * | * | * | * | * | * | 38 | 597 | 1,702 | 1,990 | 922 | 73 | *
8th child or higher order | 4,322 | * | * | * | * | * | * | * | 45 | 324 | 1,122 | 1,786 | 962 | 78 | *
Not stated | 3,342 | * | 191 | * | 12 | 28 | 59 | 88 | 715 | 949 | 823 | 509 | 142 | * | *

^*^ Estimate does not meet National Center for Health Statistics standards of reliability.

^1^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^2^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

^3^Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

#### Fertility rate

The general fertility rate (GFR) for the United States in 2024 was a record low, 53.8 births per 1,000 women ages 15–44, down 1% from 2023 (54.5) (Table 1). The GFR has declined 21% since 2008 (13).

Among race and Hispanic-origin groups, the GFR declined less than 1% for White (51.5), 1% for Hispanic (64.3), 3% for both American Indian and Alaska Native (46.8) and Asian (46.3), and 5% for Black (50.9) women from 2023 to 2024 (Tables A and 1). The rate for Native Hawaiian and Other Pacific Islander women was essentially unchanged (72.4).

### Age of mother

Birth rates declined for females ages 15–34, rose for those ages 40–44, and were unchanged for those ages 10–14, 35–39, and 45–49 from 2023 to 2024.

Teenagers—The birth rate for those ages 15–19 in the United States in 2024 was a record low, 12.6 births per 1,000, down 4% from 2023 (13.1) (Table 2, Figure 2) (7,13,17). Since 2009, the teen birth rate has fallen to a new low each year. The teen birth rate has declined 70% since 2007 (41.5), the most recent high, and 80% since the 1991 high (61.8). The number of births to teenagers ages 15–19 was 137,273 in 2024, down 3% from 2023 (140,977) (Table 3) (7).

Table 2 Birth rates, by age of mother: United States, 2010–2024, and by age and race and Hispanic origin of mother: United States, 2016–2024

[Total fertility rates are sums of birth rates for 5-year age groups multiplied by 5. Birth rates are births per 1,000 women in specified group. Populations based on counts enumerated as of April 1 for 2010 and estimated as of April 1 for 2020 and July 1 for all other years]

Race and Hispanic origin of mother and year | Total fertility rate | Age of mother
Race and Hispanic origin of mother and year | Total fertility rate | 10–14 | 15–19 | | | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49^1^
Race and Hispanic origin of mother and year | Total fertility rate | 10–14 | Total | 15–17 | 18–19 | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49^1^
All races and origins^2^
2024 | 1,599.5 | 0.2 | 12.6 | 5.3 | 23.6 | 55.8 | 89.5 | 93.7 | 54.3 | 12.7 | 1.1
2023 | 1,621.0 | 0.2 | 13.1 | 5.5 | 24.6 | 57.7 | 91.0 | 94.3 | 54.3 | 12.5 | 1.1
2022 | 1,656.5 | 0.2 | 13.6 | 5.6 | 25.8 | 57.5 | 93.5 | 97.5 | 55.3 | 12.6 | 1.1
2021 | 1,664.0 | 0.2 | 13.9 | 5.6 | 26.6 | 61.5 | 93.0 | 97.6 | 53.7 | 12.0 | 0.9
2020 | 1,641.5 | 0.2 | 15.0 | 6.1 | 28.2 | 63.3 | 90.9 | 94.9 | 51.3 | 11.8 | 0.9
2019 | 1,706.0 | 0.2 | 16.7 | 6.7 | 31.1 | 66.6 | 93.7 | 98.3 | 52.8 | 12.0 | 0.9
2018 | 1,729.5 | 0.2 | 17.4 | 7.2 | 32.3 | 68.0 | 95.3 | 99.7 | 52.6 | 11.8 | 0.9
2017 | 1,765.5 | 0.2 | 18.8 | 7.9 | 35.1 | 71.0 | 98.0 | 100.3 | 52.3 | 11.6 | 0.9
2016 | 1,820.5 | 0.2 | 20.3 | 8.8 | 37.5 | 73.8 | 102.1 | 102.7 | 52.7 | 11.4 | 0.9
2015 | 1,843.5 | 0.2 | 22.3 | 9.9 | 40.7 | 76.8 | 104.3 | 101.5 | 51.8 | 11.0 | 0.8
2014 | 1,862.5 | 0.3 | 24.2 | 10.9 | 43.8 | 79.0 | 105.8 | 100.8 | 51.0 | 10.6 | 0.8
2013 | 1,857.5 | 0.3 | 26.5 | 12.3 | 47.1 | 80.7 | 105.5 | 98.0 | 49.3 | 10.4 | 0.8
2012 | 1,880.5 | 0.4 | 29.4 | 14.1 | 51.4 | 83.1 | 106.5 | 97.3 | 48.3 | 10.4 | 0.7
2011 | 1,894.5 | 0.4 | 31.3 | 15.4 | 54.1 | 85.3 | 107.2 | 96.5 | 47.2 | 10.3 | 0.7
2010 | 1,931.0 | 0.4 | 34.2 | 17.3 | 58.2 | 90.0 | 108.3 | 96.5 | 45.9 | 10.2 | 0.7
Non-Hispanic, single race^3^
American Indian and Alaska Native:
2024 | 1,380.5 | 0.4 | 20.3 | 9.1 | 37.1 | 70.4 | 79.0 | 61.8 | 35.6 | 8.1 | 0.5
2023 | 1,411.0 | 0.3 | 20.9 | 9.4 | 38.6 | 73.2 | 78.7 | 64.0 | 36.1 | 8.4 | 0.6
2022 | 1,470.0 | 0.4 | 22.5 | 9.5 | 42.5 | 74.3 | 82.8 | 68.1 | 36.3 | 9.1 | 0.5
2021 | 1,477.0 | 0.3 | 24.2 | 11.3 | 44.1 | 78.7 | 81.9 | 66.1 | 36.2 | 7.5 | 0.5
2020 | 1,520.5 | 0.4 | 25.2 | 11.0 | 46.3 | 82.2 | 83.2 | 68.8 | 35.9 | 8.1 | 0.3
2019 | 1,611.5 | 0.3 | 29.2 | 13.5 | 51.8 | 86.7 | 89.1 | 72.0 | 36.6 | 8.0 | 0.4
2018 | 1,650.5 | 0.2 | 29.7 | 13.5 | 52.9 | 87.7 | 94.4 | 73.2 | 36.1 | 8.3 | 0.5
2017 | 1,702.0 | 0.5 | 32.9 | 15.7 | 58.1 | 93.6 | 96.4 | 72.1 | 36.3 | 8.2 | 0.4
2016 | 1,794.5 | 0.5 | 35.1 | 16.8 | 62.6 | 97.2 | 103.4 | 77.1 | 37.1 | 8.2 | 0.3
Asian:
2024 | 1,262.0 | 0.0 | 1.6 | 0.6 | 3.0 | 13.3 | 51.5 | 99.5 | 67.9 | 16.8 | 1.8
2023 | 1,309.0 | * | 1.8 | 0.6 | 3.4 | 15.6 | 56.2 | 101.3 | 68.4 | 16.7 | 1.8
2022 | 1,353.0 | * | 1.9 | 0.7 | 3.7 | 16.4 | 58.6 | 104.0 | 70.9 | 17.0 | 1.8
2021 | 1,351.5 | * | 2.0 | 0.7 | 3.8 | 17.7 | 60.4 | 105.0 | 67.9 | 15.8 | 1.5
2020 | 1,379.0 | * | 2.2 | 0.8 | 4.3 | 20.4 | 63.9 | 105.5 | 66.6 | 15.5 | 1.7
2019 | 1,511.0 | * | 2.7 | 0.9 | 5.2 | 23.1 | 71.4 | 115.6 | 71.0 | 16.5 | 1.9
2018 | 1,525.0 | * | 2.8 | 1.0 | 5.4 | 24.1 | 73.0 | 116.5 | 70.7 | 16.1 | 1.8
2017 | 1,597.0 | * | 3.3 | 1.1 | 6.5 | 26.6 | 79.6 | 120.1 | 71.5 | 16.5 | 1.8
2016 | 1,690.5 | * | 3.9 | 1.4 | 7.5 | 28.9 | 87.0 | 127.4 | 72.8 | 16.4 | 1.7
Black:
2024 | 1,501.0 | 0.3 | 17.7 | 8.2 | 32.2 | 64.4 | 80.6 | 73.4 | 48.3 | 14.0 | 1.5
2023 | 1,581.0 | 0.3 | 19.3 | 8.9 | 35.5 | 69.7 | 85.3 | 76.5 | 49.7 | 13.9 | 1.5
2022 | 1,639.0 | 0.3 | 20.3 | 9.0 | 37.7 | 71.1 | 90.7 | 79.8 | 50.4 | 13.8 | 1.4
2021 | 1,675.0 | 0.3 | 21.8 | 9.3 | 40.6 | 79.1 | 91.9 | 79.7 | 48.2 | 12.8 | 1.2
2020 | 1,713.5 | 0.3 | 23.7 | 10.5 | 42.7 | 84.0 | 93.4 | 80.4 | 47.1 | 12.7 | 1.1
2019 | 1,775.5 | 0.4 | 25.8 | 11.1 | 46.4 | 88.3 | 96.4 | 82.9 | 47.6 | 12.6 | 1.1
2018 | 1,792.0 | 0.4 | 26.3 | 11.9 | 46.9 | 90.0 | 97.1 | 84.1 | 47.1 | 12.3 | 1.1
2017 | 1,824.5 | 0.4 | 27.5 | 12.5 | 49.8 | 94.2 | 99.5 | 84.5 | 46.1 | 11.7 | 1.0
2016 | 1,832.5 | 0.5 | 29.3 | 13.7 | 52.5 | 95.8 | 100.8 | 83.0 | 45.0 | 11.1 | 1.0
Native Hawaiian and Other Pacific Islander:
2024 | 2,190.0 | * | 20.2 | 6.8 | 39.3 | 108.0 | 135.7 | 101.8 | 54.9 | 15.9 | 1.3
2023 | 2,218.0 | * | 21.2 | 7.5 | 41.4 | 115.3 | 137.3 | 95.8 | 56.7 | 15.8 | 1.4
2022 | 2,237.5 | * | 20.5 | 7.3 | 40.7 | 123.0 | 132.4 | 98.0 | 56.6 | 15.5 | 1.3
2021 | 2,131.0 | * | 21.9 | 7.3 | 44.6 | 116.1 | 124.7 | 95.8 | 51.2 | 15.0 | 1.3
2020 | 2,134.5 | * | 22.2 | 7.7 | 44.5 | 120.5 | 125.3 | 91.6 | 51.5 | 14.6 | *
2019 | 2,178.0 | * | 26.2 | 7.7 | 53.8 | 121.4 | 123.5 | 95.3 | 54.1 | 14.2 | *
2018 | 2,106.5 | * | 26.5 | 8.2 | 53.7 | 118.5 | 118.9 | 91.9 | 49.2 | 15.4 | *
2017 | 2,085.5 | * | 25.5 | 8.7 | 50.6 | 113.3 | 115.7 | 94.0 | 54.6 | 13.1 | *
2016 | 2,076.5 | * | 28.6 | 11.0 | 55.3 | 109.5 | 115.5 | 96.0 | 49.9 | 14.7 | *
White:
2024 | 1,527.5 | 0.1 | 8.3 | 2.9 | 16.1 | 46.9 | 88.7 | 97.3 | 52.4 | 10.9 | 0.9
2023 | 1,532.5 | 0.1 | 8.4 | 2.9 | 16.7 | 48.3 | 89.2 | 97.1 | 51.9 | 10.6 | 0.9
2022 | 1,568.0 | 0.1 | 9.1 | 3.1 | 17.9 | 48.3 | 91.1 | 100.4 | 53.0 | 10.7 | 0.9
2021 | 1,598.5 | 0.1 | 9.4 | 3.2 | 18.7 | 52.0 | 91.8 | 102.3 | 52.8 | 10.5 | 0.8
2020 | 1,551.0 | 0.1 | 10.1 | 3.4 | 19.9 | 53.1 | 88.2 | 98.2 | 49.7 | 10.1 | 0.7
2019 | 1,610.5 | 0.1 | 11.4 | 3.8 | 22.3 | 56.1 | 90.8 | 101.5 | 51.1 | 10.3 | 0.8
2018 | 1,640.0 | 0.1 | 12.1 | 4.1 | 23.6 | 57.8 | 92.9 | 103.1 | 51.1 | 10.2 | 0.7
2017 | 1,666.5 | 0.1 | 13.2 | 4.6 | 26.0 | 59.8 | 95.3 | 103.7 | 50.6 | 9.9 | 0.7
2016 | 1,719.0 | 0.1 | 14.3 | 5.2 | 27.7 | 62.4 | 99.3 | 106.2 | 51.1 | 9.7 | 0.7
Hispanic^4^
2024 | 1,925.5 | 0.3 | 20.0 | 8.8 | 37.3 | 79.9 | 110.5 | 99.7 | 58.4 | 15.2 | 1.1
2023 | 1,946.0 | 0.3 | 20.8 | 9.3 | 39.0 | 81.1 | 111.2 | 100.3 | 59.0 | 15.4 | 1.1
2022 | 1,969.5 | 0.3 | 21.3 | 9.3 | 40.1 | 79.2 | 113.8 | 103.1 | 59.5 | 15.5 | 1.2
2021 | 1,899.0 | 0.3 | 21.1 | 9.3 | 39.8 | 82.3 | 108.3 | 97.5 | 54.9 | 14.4 | 1.0
2020 | 1,879.5 | 0.3 | 23.0 | 10.3 | 42.5 | 83.8 | 105.8 | 94.4 | 53.4 | 14.2 | 1.0
2019 | 1,940.0 | 0.3 | 25.3 | 11.5 | 46.2 | 88.0 | 108.0 | 96.3 | 54.6 | 14.5 | 1.0
2018 | 1,959.0 | 0.3 | 26.7 | 12.4 | 48.5 | 89.3 | 108.9 | 96.6 | 54.5 | 14.5 | 1.0
2017 | 2,006.5 | 0.3 | 28.9 | 13.6 | 52.7 | 93.8 | 111.8 | 96.4 | 54.6 | 14.5 | 1.0
2016 | 2,092.5 | 0.4 | 31.9 | 15.6 | 57.3 | 98.4 | 117.4 | 99.2 | 55.8 | 14.5 | 0.9

0.0 Quantity more than zero but less than 0.05.

^*^ Estimate does not meet National Center for Health Statistics standards of reliability.

^1^Birth rates computed by relating births to women age 45 and older to women ages 45–49; see Technical Notes in this report.

^2^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^3^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

^4^Includes all people of Hispanic origin of any race; see Technical Notes.

NOTE: Rates for 2020 have been revised and may differ from those published in ‘‘Births: Final Data for 2020”; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 2 Birth rate, by selected age of mother: United States, 1990-2024

NOTES: Rates for 2020 have been revised and may differ from those published in "Births: Final Data for 2020." Rates are plotted on a logarithmic scale.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 2 is a line graph showing the birth rate by selected age of mother from 1990 through 2024.

The 2024 birth rate for teenagers ages 15–17 was a record low, 5.3 births per 1,000 females, down 4% from 2023 (Table 2). The rate for those ages 18–19 was also a record low, 23.6 births, down 4% from 2023. Rates for these age groups have fallen 76% and 67%, respectively, since 2007, and by 86% and 75% since 1991 (13). The birth rate for females ages 10–14 was unchanged in 2024 at 0.2 births per 1,000 females.

Among race and Hispanic-origin groups, birth rates for teenagers ages 15–19 declined for most groups: down 11% for Asian, 8% for Black, 4% for Hispanic, and 1% for White females from 2023 to 2024. The change in rates for American Indian and Alaska Native and Native Hawaiian and Other Pacific Islander females was not significant.

Women in their 20s—The birth rate for women ages 20–24 was a record low, 55.8 births per 1,000 women in 2024, down 3% from 2023 (57.7) (Table 2) (13,17). The rate for women in this age group has generally declined since 2007. The number of births to women in their early 20s declined 1% from 2023 (Table 3) (7). The rate for women ages 25–29 was a record low, 89.5 births per 1,000 women, down 2% from 2023 (91.0). The rate for women in this age group has generally declined since 2008 (13). The number of births to women ages 25–29 rose less than 1% from 2023 to 2024 (7).

Women in their 30s—The birth rate for women ages 30–34 was 93.7 births per 1,000 women in 2024, down 1% from 2023 (94.3); the rate has declined 7% since 2017 (Table 2). The rate for ages 30–34 has been higher than the rate for ages 25–29 since 2016 (13,17). The number of births to women ages 30–34 rose by 1% from 2023 to 2024 (Table 3) (7). The birth rate for women ages 35–39 was 54.3 births per 1,000 women in 2024, unchanged from 2023 (Table 2). The number of births to women ages 35–39 rose 3% from 2023 to 2024 (7).

Women in their 40s—The birth rate for women ages 40–44 was 12.7 births per 1,000 women in 2024, up 2% from 2023 (12.5) and the highest rate since 1965 (Table 2). The rate for this group has generally risen since 1985 (13,17). The number of births to women in their early 40s rose 4% from 2023 to 2024 (Table 3) (7). The birth rate for women ages 45–49 (includes births to women age 50 and older) was 1.1 in 2024, unchanged from 2023 and 2022. The number of births to women age 45 and older was essentially unchanged from 2023 to 2024 (7).

Women age 50 and older—The birth rate for women ages 50–54 was 1.2 births per 10,000 women in 2024, unchanged from 2023 and 2022. Because of the small number of births to women in this age group, the birth rate for women ages 50–54 is expressed per 10,000 women. For rates shown elsewhere in this report, births to women age 50 and older are included with births to women ages 45–49 when computing birth rates by age of mother (the denominator for the rate is women ages 45–49). A total of 1,188 births were to women age 50 and older in 2024, essentially unchanged from 1,217 in 2023 (Table 3) (7). The number of births to women in this age group has generally increased since 1997, when 144 births were reported (7).

### Live-birth order

The first-birth rate for the United States was 21.3 births per 1,000 females ages 15–44 in 2024, down less than 1% from 2023 (21.4) (7) (see Table 3 for the number of births; see also Tables 5 [number of births] and 6 [birth rates] in the 2024 User Guide [8]). First-birth rates declined for females in their teens (4% for ages 15–19), early 20s (2% for ages 20–24), and late 20s (1% for ages 25–29), and rose for women in their early 30s (1% for ages 30–34), late 30s (2% for ages 35–39) and early 40s (4% for ages 40–44).

#### Mean age of mother

The mean age of mothers at first birth was a record high in 2024, 27.6 years, an increase from 27.5 in 2023 (Tables A, B, and 4) (13,17). Mean age at first birth is the arithmetic average of the age of mothers at the time of birth and is computed directly from the frequency of first births by age of mother. The increase in the mean age in 2024 reflects the decline in the proportion of first births to females younger than 20 and the concurrent rise in the proportion of first births to women age 20 and older (7).

Table 4 Mean age of mother, by live-birth order: United States, 2010–2024, and by race and Hispanic origin of mother: United States, 2016–2024

[Mean age at birth is the arithmetic average of the age of mothers at time of birth, computed directly from the frequency of births by age of mother and live-birth order. Live-birth order refers to number of children born alive to mother]

Race and Hispanic origin and year | Total | Live-birth order
Race and Hispanic origin and year | Total | 1 | 2 | 3 | 4 | 5 | 6 and 7 | 8 and over | Unknown or not stated
All races and origins^1^
2024 | 29.7 | 27.6 | 30.0 | 31.2 | 32.3 | 33.3 | 34.4 | 36.7 | 30.1
2023 | 29.6 | 27.5 | 30.0 | 31.2 | 32.2 | 33.2 | 34.3 | 36.5 | 30.3
2022 | 29.5 | 27.4 | 29.9 | 31.1 | 32.1 | 33.0 | 34.2 | 36.4 | 30.4
2021 | 29.4 | 27.3 | 29.7 | 30.9 | 31.9 | 32.9 | 34.0 | 36.3 | 30.2
2020 | 29.2 | 27.1 | 29.6 | 30.7 | 31.8 | 32.7 | 34.0 | 36.2 | 29.9
2019 | 29.1 | 27.0 | 29.5 | 30.6 | 31.6 | 32.6 | 33.8 | 36.1 | 29.5
2018 | 29.0 | 26.9 | 29.3 | 30.5 | 31.5 | 32.5 | 33.7 | 36.1 | 29.3
2017 | 28.8 | 26.8 | 29.2 | 30.3 | 31.4 | 32.4 | 33.7 | 36.0 | 29.1
2016 | 28.7 | 26.6 | 29.0 | 30.2 | 31.3 | 32.3 | 33.5 | 35.9 | 28.7
2015 | 28.5 | 26.4 | 28.8 | 30.1 | 31.2 | 32.2 | 33.4 | 35.8 | 29.3
2014 | 28.3 | 26.3 | 28.7 | 30.0 | 31.1 | 32.0 | 33.4 | 35.7 | 28.7
2013 | 28.2 | 26.0 | 28.6 | 29.9 | 31.0 | 32.0 | 33.3 | 35.7 | 28.3
2012 | 28.0 | 25.8 | 28.4 | 29.8 | 30.9 | 31.9 | 33.2 | 35.7 | 27.9
2011 | 27.9 | 25.6 | 28.3 | 29.7 | 30.8 | 31.8 | 33.1 | 35.5 | 28.2
2010 | 27.7 | 25.4 | 28.2 | 29.6 | 30.7 | 31.7 | 33.0 | 35.7 | 27.7
Non-Hispanic, single race^2^
American Indian and Alaska Native:
2024 | 27.8 | 24.3 | 27.3 | 29.4 | 31.0 | 32.4 | 33.7 | 35.8 | 28.1
2023 | 27.8 | 24.2 | 27.2 | 29.2 | 31.1 | 32.5 | 33.6 | 35.4 | 28.6
2022 | 27.7 | 24.2 | 27.1 | 29.0 | 30.8 | 32.1 | 33.4 | 35.5 | 27.8
2021 | 27.5 | 23.9 | 26.8 | 28.9 | 30.6 | 31.9 | 33.1 | 35.3 | 27.0
2020 | 27.3 | 23.8 | 26.7 | 28.7 | 30.4 | 31.6 | 32.9 | 35.2 | 27.3
2019 | 27.1 | 23.5 | 26.5 | 28.6 | 30.0 | 31.2 | 32.9 | 34.9 | 27.0
2018 | 27.1 | 23.5 | 26.4 | 28.4 | 30.0 | 31.1 | 32.8 | 34.8 | 27.6
2017 | 26.8 | 23.3 | 26.1 | 28.1 | 29.6 | 31.3 | 32.6 | 34.4 | 27.8
2016 | 26.7 | 23.2 | 26.1 | 28.0 | 29.6 | 31.1 | 32.0 | 34.8 | 28.1
Asian:
2024 | 32.8 | 31.7 | 33.5 | 34.2 | 34.7 | 35.2 | 35.9 | 36.6 | 32.9
2023 | 32.7 | 31.5 | 33.4 | 34.2 | 34.5 | 34.9 | 35.5 | 37.0 | 33.1
2022 | 32.6 | 31.4 | 33.3 | 34.1 | 34.5 | 35.0 | 35.5 | 36.5 | 33.1
2021 | 32.4 | 31.2 | 33.1 | 34.0 | 34.3 | 34.7 | 35.4 | 36.1 | 32.4
2020 | 32.2 | 30.9 | 32.9 | 33.8 | 34.1 | 34.7 | 35.4 | 36.8 | 32.6
2019 | 32.0 | 30.7 | 32.7 | 33.6 | 34.1 | 34.5 | 35.3 | 36.6 | 32.3
2018 | 31.8 | 30.5 | 32.6 | 33.5 | 34.0 | 34.4 | 35.0 | 36.5 | 31.6
2017 | 31.7 | 30.3 | 32.5 | 33.4 | 33.9 | 34.4 | 35.2 | 36.3 | 32.0
2016 | 31.5 | 30.1 | 32.3 | 33.3 | 33.6 | 34.1 | 34.9 | 36.3 | 31.4
Black:
2024 | 29.1 | 26.1 | 29.2 | 31.0 | 32.1 | 32.8 | 33.7 | 35.7 | 29.8
2023 | 28.9 | 25.9 | 29.0 | 30.7 | 31.8 | 32.6 | 33.6 | 35.4 | 30.1
2022 | 28.7 | 25.8 | 28.8 | 30.6 | 31.6 | 32.3 | 33.3 | 35.4 | 30.3
2021 | 28.4 | 25.5 | 28.5 | 30.3 | 31.3 | 32.1 | 33.2 | 35.2 | 29.6
2020 | 28.2 | 25.3 | 28.3 | 30.0 | 31.0 | 31.8 | 32.9 | 35.1 | 29.2
2019 | 28.0 | 25.2 | 28.1 | 29.7 | 30.8 | 31.6 | 32.7 | 35.0 | 28.7
2018 | 27.9 | 25.1 | 28.0 | 29.6 | 30.6 | 31.5 | 32.6 | 34.9 | 28.4
2017 | 27.7 | 24.9 | 27.7 | 29.3 | 30.4 | 31.3 | 32.5 | 34.9 | 28.0
2016 | 27.4 | 24.8 | 27.6 | 29.1 | 30.2 | 31.1 | 32.3 | 34.6 | 27.1
Native Hawaiian and Other Pacific Islander:
2024 | 28.5 | 25.3 | 27.6 | 29.2 | 30.6 | 32.2 | 33.8 | 35.9 | 27.9
2023 | 28.5 | 25.2 | 27.6 | 29.1 | 30.9 | 32.4 | 33.6 | 35.9 | 27.2
2022 | 28.4 | 25.2 | 27.4 | 29.3 | 30.8 | 32.0 | 33.6 | 35.9 | 27.2
2021 | 28.3 | 25.2 | 27.2 | 29.1 | 30.8 | 32.1 | 33.3 | 36.0 | 27.8
2020 | 28.2 | 25.0 | 27.4 | 29.1 | 30.6 | 31.8 | 33.6 | 35.4 | 27.6
2019 | 28.1 | 24.8 | 27.3 | 29.0 | 30.4 | 31.7 | 33.2 | 35.7 | 26.6
2018 | 27.9 | 24.7 | 26.9 | 28.9 | 30.5 | 31.7 | 33.0 | 35.8 | 27.2
2017 | 28.0 | 24.9 | 27.2 | 28.9 | 30.5 | 31.4 | 33.0 | 35.4 | 26.8
2016 | 27.9 | 24.8 | 27.0 | 28.9 | 30.1 | 31.7 | 33.2 | 35.3 | 27.6
2024 | 30.1 | 28.4 | 30.5 | 31.5 | 32.3 | 33.3 | 34.6 | 37.3 | 30.5
2023 | 30.0 | 28.3 | 30.4 | 31.4 | 32.3 | 33.1 | 34.4 | 37.2 | 30.5
2022 | 29.9 | 28.2 | 30.4 | 31.3 | 32.1 | 33.0 | 34.4 | 37.1 | 30.7
2021 | 29.9 | 28.1 | 30.3 | 31.2 | 32.1 | 33.0 | 34.2 | 37.0 | 30.7
2020 | 29.7 | 27.9 | 30.1 | 31.1 | 31.9 | 32.8 | 34.2 | 37.0 | 30.3
2019 | 29.6 | 27.8 | 30.0 | 30.9 | 31.8 | 32.7 | 34.1 | 36.9 | 30.0
2018 | 29.4 | 27.7 | 29.8 | 30.8 | 31.7 | 32.7 | 34.1 | 36.8 | 29.6
2017 | 29.3 | 27.6 | 29.7 | 30.7 | 31.6 | 32.6 | 34.0 | 36.8 | 29.5
2016 | 29.2 | 27.4 | 29.5 | 30.6 | 31.5 | 32.5 | 33.9 | 36.7 | 29.4
Hispanic^3^
2024 | 28.6 | 25.8 | 28.6 | 30.6 | 32.3 | 33.6 | 34.8 | 36.1 | 28.7
2023 | 28.5 | 25.7 | 28.6 | 30.6 | 32.2 | 33.5 | 34.7 | 36.0 | 29.0
2022 | 28.5 | 25.7 | 28.5 | 30.5 | 32.2 | 33.4 | 34.6 | 35.8 | 29.1
2021 | 28.4 | 25.5 | 28.3 | 30.4 | 32.0 | 33.3 | 34.5 | 35.7 | 29.2
2020 | 28.3 | 25.3 | 28.2 | 30.3 | 31.9 | 33.2 | 34.5 | 35.7 | 29.1
2019 | 28.2 | 25.1 | 28.1 | 30.2 | 31.8 | 33.1 | 34.3 | 35.6 | 28.5
2018 | 28.1 | 25.0 | 28.0 | 30.1 | 31.7 | 33.0 | 34.1 | 35.6 | 29.2
2017 | 28.0 | 24.8 | 27.8 | 29.9 | 31.6 | 32.9 | 34.1 | 35.5 | 29.0
2016 | 27.8 | 24.7 | 27.6 | 29.8 | 31.5 | 32.7 | 34.0 | 35.3 | 28.3

^1^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^2^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. People of Hispanic origin may be of any race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

^3^Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Mean age at first birth increased for four race and Hispanic-origin groups in 2024, rising to 25.8 for Hispanic, 26.1 for Black, 28.4 for White, and 31.7 for Asian women (Table 4). The average age at first birth for American Indian and Alaska Native (24.3) and Native Hawaiian and Other Pacific Islander (25.3) women was unchanged from 2023. Among the specified Hispanic groups, average age increased to 25.4 for Mexican and 26.1 for Central and South American women (Table B) (7). The age at first birth for Puerto Rican (26.0), Dominican (26.9), and Cuban (28.1) women in 2024 was essentially unchanged from 2023.

### Total fertility rate

The total fertility rate (TFR) for the United States in 2024 was 1,599.5 births per 1,000 women, down 1% from 2023 (1,621.0) and a record low (Table 2). TFR has generally declined since 2008, down 23%. TFR estimates the number of births that a hypothetical group of 1,000 women would have over their lifetimes, based on age-specific birth rates in a given year. Because it is calculated from age-specific birth rates, TFR is age adjusted and can be compared for populations across time, population groups, and geographic areas.

Among race and Hispanic-origin groups, the TFR declined less than 1% for White, 1% for Hispanic, 2% for American Indian and Alaska Native, 4% for Asian, and 5% for Black women from 2023 to 2024. The rate for Native Hawaiian and Other Pacific Islander women was essentially unchanged.

The TFR for the nation in 2024 remained below replacement, the level at which a given generation can exactly replace itself (generally considered to be 2,100 births per 1,000 women). The U.S. TFR has generally been below replacement since 1971 and has consistently been below replacement since 2008 (13,17). The TFR was below replacement for all race and Hispanic-origin groups in 2024 except for Native Hawaiian and Other Pacific Islander women (2,190.0 births) (Table 2).

### Births and birth rates by state

GFR, the number of births per 1,000 females ages 15–44, declined in 19 states and D.C. from 2023 to 2024, with decreases of 1%–2% reported in 14 states (Alabama, Arizona, California, Illinois, Kansas, Maryland, Massachusetts, Michigan, New York, Ohio, Oklahoma, Pennsylvania, Texas, and Wisconsin), 3%–4% in 5 states (Connecticut, Florida, Louisiana, Mississippi, and New Jersey), and 7% in D.C. GFRs rose in two states (Colorado and West Virginia) and were essentially unchanged in the remaining 29 states (7). Rates among the states ranged from 39.8 births per 1,000 females ages 15–44 in D.C. to 66.7 in South Dakota. (See Tables 5 and 6 for number of births and birth rates; see also Table 3 in the 2024 User Guide for births to Hispanic subgroups [8]). Among U.S. territories, the GFR declined in Puerto Rico and was essentially unchanged in Guam, Northern Marianas, and U.S. Virgin Islands.

Table 6 Birth rates, by age of mother: United States, each state and territory, 2024

[By place of residence. Fertility rates are births per 1,000 females ages 15–44; total fertility rates are sums of birth rates for 5-year age groups multiplied by 5; birth rates by age are births per 1,000 women in specified age group estimated in each area. Populations estimated as of July 1]

Area | Birth rate | Fertility rate | Total fertility rate | Age of mother
Area | Birth rate | Fertility rate | Total fertility rate | 10–14 | 15–19 | | | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49^1^
Area | Birth rate | Fertility rate | Total fertility rate | 10–14 | Total | 15–17 | 18–19 | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49^1^
United States^2^ | 10.7 | 53.8 | 1,599.5 | 0.2 | 12.6 | 5.3 | 23.6 | 55.8 | 89.5 | 93.7 | 54.3 | 12.7 | 1.1
Alabama | 11.2 | 57.2 | 1,716.0 | 0.3 | 19.1 | 9.0 | 33.5 | 77.5 | 111.6 | 86.1 | 39.9 | 8.3 | 0.4
Alaska | 12.1 | 60.8 | 1,795.0 | * | 14.5 | 4.3 | 33.3 | 80.5 | 103.8 | 93.0 | 53.0 | 13.2 | 0.9
Arizona | 10.4 | 53.2 | 1,569.0 | 0.1 | 13.9 | 5.6 | 26.1 | 59.0 | 92.1 | 89.2 | 47.7 | 10.9 | 0.9
Arkansas | 11.5 | 58.8 | 1,763.0 | 0.2 | 22.2 | 8.9 | 43.3 | 89.1 | 113.6 | 82.0 | 37.2 | 7.9 | 0.4
California | 10.2 | 49.8 | 1,462.5 | 0.1 | 8.7 | 3.5 | 16.2 | 41.5 | 70.9 | 89.4 | 63.3 | 16.8 | 1.8
Colorado | 10.8 | 51.6 | 1,491.0 | 0.1 | 11.2 | 4.9 | 20.4 | 50.2 | 76.1 | 89.7 | 57.1 | 12.8 | 1.0
Connecticut | 9.4 | 48.9 | 1,477.5 | * | 6.5 | 2.6 | 11.7 | 29.7 | 67.9 | 108.5 | 66.4 | 14.9 | 1.5
Delaware | 10.0 | 53.7 | 1,613.0 | * | 13.1 | 5.6 | 23.2 | 54.6 | 92.6 | 94.4 | 52.7 | 14.2 | 0.9
District of Columbia | 10.8 | 39.8 | 1,107.5 | * | 12.3 | 10.4 | 13.8 | 30.7 | 30.3 | 60.1 | 63.4 | 21.8 | 2.6
Florida | 9.6 | 52.2 | 1,550.5 | 0.2 | 11.8 | 4.8 | 22.6 | 52.7 | 87.3 | 90.3 | 53.2 | 13.5 | 1.1
Georgia | 11.3 | 54.7 | 1,636.0 | 0.2 | 16.0 | 6.7 | 30.7 | 65.6 | 95.2 | 89.0 | 48.5 | 11.7 | 1.0
Hawaii | 10.3 | 56.6 | 1,676.0 | * | 11.0 | 3.2 | 24.2 | 61.9 | 92.8 | 91.2 | 59.4 | 16.8 | 1.9
Idaho | 11.6 | 58.6 | 1,819.5 | * | 9.9 | 3.8 | 17.8 | 75.5 | 121.6 | 98.4 | 46.8 | 10.8 | 0.8
Illinois | 9.9 | 49.7 | 1,474.5 | 0.1 | 10.4 | 4.4 | 19.7 | 44.9 | 76.9 | 93.3 | 56.0 | 12.3 | 1.0
Indiana | 11.6 | 59.1 | 1,770.0 | 0.2 | 15.0 | 5.9 | 29.5 | 69.8 | 115.0 | 96.9 | 46.6 | 9.8 | 0.7
Iowa | 11.2 | 58.8 | 1,798.5 | 0.2 | 12.2 | 5.2 | 22.3 | 56.4 | 123.0 | 109.5 | 48.2 | 9.5 | 0.7
Kansas | 11.4 | 58.3 | 1,773.0 | 0.2 | 14.7 | 6.0 | 28.3 | 66.6 | 112.0 | 102.5 | 48.4 | 9.5 | 0.7
Kentucky | 11.5 | 60.3 | 1,796.0 | 0.2 | 20.4 | 7.7 | 41.3 | 84.7 | 113.0 | 88.7 | 43.1 | 8.6 | 0.5
Louisiana | 11.6 | 58.2 | 1,766.0 | 0.4 | 21.3 | 8.9 | 41.1 | 82.5 | 111.2 | 85.7 | 42.6 | 9.1 | 0.4
Maine | 8.3 | 46.3 | 1,381.0 | * | 7.8 | 2.9 | 14.7 | 43.0 | 83.1 | 85.4 | 45.9 | 10.3 | 0.6
Maryland | 10.5 | 53.3 | 1,592.0 | 0.2 | 10.3 | 4.7 | 19.2 | 45.6 | 81.3 | 100.7 | 62.6 | 15.9 | 1.8
Massachusetts | 9.6 | 46.8 | 1,377.5 | 0.1 | 5.4 | 2.5 | 8.8 | 24.6 | 56.7 | 102.4 | 68.9 | 16.0 | 1.4
Michigan | 9.8 | 51.5 | 1,522.0 | 0.1 | 10.3 | 3.9 | 20.0 | 48.1 | 92.6 | 94.1 | 48.9 | 9.7 | 0.6
Minnesota | 10.7 | 55.2 | 1,672.0 | 0.1 | 7.3 | 3.1 | 14.2 | 42.4 | 96.7 | 114.8 | 59.5 | 12.5 | 1.1
Mississippi | 11.4 | 57.3 | 1,737.0 | 0.4 | 22.8 | 9.9 | 42.3 | 87.0 | 113.9 | 80.0 | 35.9 | 7.0 | 0.4
Missouri | 10.9 | 55.9 | 1,671.5 | 0.2 | 15.9 | 6.4 | 31.0 | 67.2 | 104.5 | 93.4 | 43.8 | 8.7 | 0.6
Montana | 10.0 | 53.3 | 1,591.5 | * | 11.1 | 4.3 | 22.5 | 54.8 | 102.0 | 90.4 | 49.8 | 9.3 | 0.7
Nebraska | 12.4 | 62.9 | 1,921.5 | 0.2 | 14.0 | 6.3 | 25.9 | 58.8 | 123.7 | 118.9 | 56.5 | 11.5 | 0.7
Nevada | 9.9 | 50.1 | 1,477.5 | * | 12.5 | 4.9 | 26.4 | 59.8 | 84.1 | 79.6 | 46.9 | 11.7 | 0.8
New Hampshire | 8.4 | 45.9 | 1,350.5 | * | 4.6 | 1.5 | 8.8 | 26.2 | 75.2 | 99.5 | 53.0 | 10.8 | 0.8
New Jersey | 10.7 | 55.7 | 1,643.5 | 0.1 | 7.3 | 3.1 | 14.4 | 40.1 | 75.1 | 112.4 | 74.5 | 17.6 | 1.6
New Mexico | 10.0 | 51.9 | 1,561.5 | 0.2 | 18.0 | 7.7 | 33.6 | 71.1 | 93.5 | 78.7 | 41.1 | 9.1 | 0.6
New York | 10.3 | 52.1 | 1,508.5 | 0.1 | 8.0 | 3.3 | 14.5 | 44.2 | 69.1 | 93.6 | 66.3 | 18.5 | 1.9
North Carolina | 11.1 | 55.8 | 1,655.0 | 0.2 | 14.3 | 6.0 | 26.1 | 62.2 | 95.5 | 94.8 | 51.8 | 11.4 | 0.8
North Dakota | 12.1 | 60.4 | 1,806.5 | * | 11.7 | 4.6 | 20.7 | 54.2 | 121.4 | 111.1 | 52.3 | 9.9 | 0.7
Ohio | 10.7 | 55.6 | 1,652.0 | 0.2 | 14.0 | 5.7 | 27.1 | 63.8 | 100.1 | 94.3 | 47.9 | 9.4 | 0.7
Oklahoma | 11.7 | 58.4 | 1,756.5 | 0.3 | 19.6 | 8.0 | 37.9 | 83.2 | 114.1 | 85.3 | 40.3 | 8.1 | 0.4
Oregon | 9.1 | 46.1 | 1,359.0 | * | 9.0 | 3.5 | 17.5 | 45.6 | 78.4 | 78.4 | 48.3 | 11.1 | 0.9
Pennsylvania | 9.7 | 51.2 | 1,531.5 | 0.2 | 9.7 | 4.5 | 16.5 | 46.9 | 85.5 | 98.3 | 53.3 | 11.4 | 1.0
Rhode Island | 9.0 | 45.0 | 1,331.0 | * | 7.5 | 3.9 | 11.3 | 31.4 | 67.0 | 90.7 | 55.7 | 12.8 | 1.0
South Carolina | 10.7 | 55.5 | 1,666.0 | 0.3 | 17.4 | 7.6 | 31.8 | 65.9 | 101.5 | 90.7 | 46.3 | 10.5 | 0.6
South Dakota | 12.4 | 66.7 | 2,040.0 | * | 15.3 | 7.0 | 28.8 | 69.0 | 136.3 | 122.5 | 53.6 | 10.3 | 0.7
Tennessee | 11.6 | 58.5 | 1,720.5 | 0.3 | 19.9 | 8.2 | 39.0 | 76.4 | 101.5 | 89.4 | 45.9 | 10.1 | 0.6
Texas | 12.5 | 59.3 | 1,769.0 | 0.2 | 18.5 | 7.9 | 35.4 | 72.4 | 102.2 | 96.0 | 51.6 | 12.0 | 0.9
Utah | 13.3 | 59.9 | 1,796.5 | * | 8.2 | 3.3 | 15.8 | 57.6 | 124.6 | 104.8 | 51.4 | 11.8 | 0.8
Vermont | 7.7 | 41.7 | 1,273.0 | * | 6.3 | 3.3 | 9.8 | 30.6 | 70.7 | 82.8 | 52.0 | 11.3 | 0.8
Virginia | 10.7 | 53.7 | 1,603.0 | 0.1 | 10.7 | 4.1 | 20.2 | 50.1 | 87.7 | 98.2 | 58.5 | 14.0 | 1.3
Washington | 10.4 | 51.3 | 1,480.5 | 0.1 | 9.3 | 3.5 | 18.8 | 50.6 | 78.1 | 88.4 | 55.2 | 13.2 | 1.2
West Virginia | 9.6 | 54.3 | 1,632.0 | 0.2 | 17.8 | 6.8 | 35.0 | 79.4 | 110.4 | 77.0 | 35.0 | 6.3 | 0.3
Wisconsin | 10.0 | 52.8 | 1,599.5 | 0.2 | 9.7 | 4.2 | 17.7 | 45.2 | 96.2 | 106.7 | 51.2 | 10.1 | 0.6
Wyoming | 10.4 | 54.8 | 1,695.5 | * | 14.7 | 4.5 | 31.2 | 74.7 | 112.7 | 87.6 | 40.8 | 8.0 | *
Puerto Rico | 5.7 | 29.7 | 870.5 | * | 11.0 | 3.9 | 21.1 | 49.1 | 51.3 | 36.3 | 21.6 | 4.5 | 0.3
Virgin Islands | 7.7 | 43.4 | 1,366.0 | * | 10.4 | * | 26.2 | 64.2 | 84.0 | 60.0 | 39.8 | 13.2 | *
Guam | 13.8 | 71.2 | 2,104.0 | * | 22.0 | 10.7 | 40.8 | 77.0 | 112.8 | 118.7 | 69.5 | 18.0 | 2.4
American Samoa | 17.3 | 78.2 | 2,287.0 | * | 26.1 | 17.9 | 36.4 | 100.8 | 125.4 | 102.7 | 76.3 | 23.5 | *
Northern Marianas | 10.9 | 61.4 | 2,057.0 | * | 13.4 | * | 26.2 | 55.0 | 73.4 | 136.6 | 108.0 | 25.0 | *

^*^ Estimate does not meet National Center for Health Statistics standards of reliability.

^1^Birth rates computed by relating births to women age 45 and older to women ages 45–49; see Technical Notes in this report.

^2^Excludes data for the territories.

NOTES: The U.S. Census Bureau provided population data for computing birth rates. Rates by state may differ from rates computed on the basis of other population estimates.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

### Births to unmarried women

The birth rate for unmarried women was 35.5 births per 1,000 unmarried females ages 15–44 in 2024, down 2% from 2023 (36.4) (Table 7). The 2024 nonmarital birth rate was 31% lower than the peak of 51.8 in 2007 and 2008 (13). (See Technical Notes for a description of the adjustments to calculations of rates by marital status beginning with 2017 data.)

Table 7 Birth rates for unmarried women: United States, 2010–2024, and by age and race and Hispanic origin of mother: United States, 2016–2024

[Rates are births to unmarried women per 1,000 unmarried women. Populations estimated as of July 1 for all years]

Race and Hispanic origin and year | Fertility rate^1^ | Age of mother
Race and Hispanic origin and year | Fertility rate^1^ | 15–19 | | | 20–24 | 25–29 | 30–34 | 35–39 | 40–44^2^
Race and Hispanic origin and year | Fertility rate^1^ | Total | 15–17 | 18–19 | 20–24 | 25–29 | 30–34 | 35–39 | 40–44^2^
All races^3^
2024 | 35.5 | 11.7 | 5.2 | 21.5 | 42.5 | 55.8 | 57.4 | 38.4 | 11.9
2023 | 36.4 | 12.3 | 5.5 | 22.7 | 44.6 | 57.4 | 57.5 | 38.8 | 11.8
2022 | 37.2 | 12.7 | 5.6 | 23.6 | 44.0 | 58.4 | 58.6 | 38.8 | 11.6
2021 | 37.8 | 13.0 | 5.6 | 24.4 | 47.4 | 58.7 | 58.5 | 38.2 | 11.4
2020 | 38.4 | 14.0 | 6.1 | 26.0 | 49.2 | 59.9 | 58.3 | 36.9 | 11.3
2019 | 39.9 | 15.4 | 6.6 | 28.3 | 51.6 | 61.5 | 60.6 | 36.0 | 11.1
2018 | 40.1 | 16.0 | 7.1 | 29.2 | 52.2 | 62.8 | 59.5 | 35.2 | 10.6
2017 | 41.0 | 17.1 | 7.7 | 31.4 | 54.2 | 64.4 | 57.9 | 36.0 | 10.1
2016 | 42.4 | 18.5 | 8.6 | 33.5 | 56.6 | 65.8 | 59.2 | 35.6 | 10.0
2015 | 43.4 | 20.2 | 9.6 | 36.5 | 59.7 | 66.9 | 60.3 | 34.1 | 9.0
2014 | 43.9 | 22.0 | 10.6 | 39.4 | 61.6 | 67.6 | 58.1 | 33.4 | 8.5
2013 | 44.3 | 24.0 | 11.9 | 42.1 | 63.1 | 66.7 | 56.6 | 31.8 | 8.3
2012 | 45.3 | 26.7 | 13.7 | 45.8 | 64.7 | 67.2 | 56.3 | 30.9 | 8.5
2011 | 46.0 | 28.4 | 14.9 | 48.2 | 66.7 | 67.8 | 56.2 | 29.9 | 8.2
2010 | 47.5 | 31.1 | 16.8 | 52.0 | 70.0 | 69.2 | 56.3 | 29.6 | 8.0
Non-Hispanic, single race^4^
American Indian and Alaska Native:
2024 | 47.0 | 19.8 | 9.3 | 35.4 | 62.4 | 79.6 | 65.1 | 38.8 | 11.4
2023 | 49.8 | 20.6 | 9.5 | 37.8 | 65.4 | 80.6 | 78.1 | 39.3 | 15.2
2022 | 51.8 | 22.7 | 9.9 | 42.6 | 70.4 | 75.8 | 86.2 | 39.9 | 12.5
2021 | 52.5 | 24.3 | 12.0 | 42.1 | 76.1 | 73.6 | 83.4 | 40.2 | 9.4
2020 | 54.3 | 24.4 | 11.2 | 43.8 | 79.3 | 80.5 | 82.6 | 40.1 | 9.3
2019 | 56.0 | 28.5 | 13.3 | 48.1 | 69.4 | 58.5 | 41.5 | 19.9 | 4.4
2018 | 56.6 | 28.0 | 13.4 | 49.1 | 69.0 | 62.2 | 41.5 | 18.4 | 4.5
2017 | 58.4 | 31.9 | 15.8 | 55.6 | 87.0 | 95.5 | 81.6 | 32.8 | 7.8
2016 | 59.2 | 34.4 | 16.7 | 61.4 | 87.6 | 94.8 | 85.2 | 28.7 | 7.2
Asian:
2024 | 11.4 | 1.2 | 0.5 | 2.1 | 5.2 | 13.0 | 28.5 | 33.0 | 15.0
2023 | 12.1 | 1.3 | 0.5 | 2.3 | 6.3 | 15.3 | 31.3 | 30.2 | 13.2
2022 | 12.9 | 1.4 | 0.6 | 2.5 | 6.7 | 17.2 | 32.0 | 32.2 | 12.4
2021 | 13.5 | 1.3 | 0.6 | 2.5 | 7.4 | 17.9 | 31.9 | 38.5 | 14.5
2020 | 13.6 | 1.7 | 0.7 | 3.1 | 8.3 | 17.6 | 33.9 | 34.6 | 13.3
2019 | 14.4 | 1.9 | 0.8 | 3.5 | 9.3 | 17.9 | 38.2 | 34.4 | 11.9
2018 | 14.1 | 1.9 | 0.9 | 3.5 | 9.4 | 19.1 | 33.6 | 33.6 | 10.9
2017 | 14.7 | 2.3 | 1.0 | 4.1 | 9.9 | 20.9 | 33.5 | 36.3 | 10.7
2016 | 15.3 | 2.7 | 1.2 | 4.9 | 10.7 | 22.5 | 38.0 | 29.8 | 9.5
Black:
2024 | 46.4 | 17.6 | 8.4 | 31.9 | 61.5 | 71.6 | 65.9 | 40.8 | 12.1
2023 | 48.8 | 19.4 | 9.1 | 35.6 | 67.1 | 74.8 | 65.6 | 40.5 | 12.0
2022 | 50.2 | 20.3 | 9.1 | 37.6 | 67.6 | 78.9 | 64.8 | 38.5 | 11.8
2021 | 52.1 | 21.8 | 9.4 | 40.8 | 76.8 | 82.9 | 63.9 | 36.7 | 10.7
2020 | 54.6 | 23.7 | 10.6 | 43.2 | 80.8 | 88.3 | 65.1 | 37.0 | 10.4
2019 | 56.7 | 25.7 | 11.3 | 46.2 | 83.5 | 87.4 | 68.4 | 37.5 | 10.5
2018 | 56.4 | 26.1 | 12.0 | 46.1 | 85.0 | 85.9 | 68.2 | 35.6 | 9.7
2017 | 57.5 | 27.3 | 12.6 | 48.7 | 88.8 | 89.3 | 66.2 | 35.1 | 8.9
2016 | 57.9 | 29.0 | 13.9 | 51.2 | 90.0 | 89.6 | 64.4 | 33.8 | 8.9
Native Hawaiian and Other Pacific Islander:
2024 | 71.5 | 18.9 | 6.7 | 37.2 | 96.5 | 120.0 | 101.1 | 118.0 | 14.6
2023 | 65.7 | 18.9 | 7.3 | 36.1 | 93.3 | 122.8 | 72.0 | 126.7 | 15.1
2022 | 64.3 | 18.5 | 7.2 | 35.7 | 92.9 | 119.2 | 74.0 | 75.5 | 15.0
2021 | 58.9 | 19.6 | 7.1 | 39.0 | 85.1 | 85.1 | 108.3 | 48.2 | 16.7
2020 | 58.6 | 20.8 | 7.4 | 43.4 | 87.9 | 74.5 | 115.8 | 49.1 | 15.8
2019 | 69.1 | 24.6 | 7.4 | 53.9 | 109.5 | 98.1 | 82.0 | 54.4 | 17.0
2018 | 80.1 | 25.5 | 8.2 | 51.1 | 106.3 | 151.9 | 76.4 | 62.8 | 31.3
2017 | 76.7 | 23.2 | 9.1 | 43.0 | 83.8 | 173.0 | 86.1 | 65.5 | 27.4
2016 | 70.5 | 24.7 | 10.5 | 46.2 | 90.3 | 141.9 | 81.1 | 46.4 | 20.8
White:
2024 | 24.1 | 7.3 | 2.9 | 13.9 | 29.0 | 38.6 | 39.7 | 27.2 | 8.4
2023 | 24.9 | 7.5 | 2.9 | 14.6 | 30.6 | 39.7 | 40.3 | 27.8 | 8.1
2022 | 25.8 | 8.1 | 3.1 | 15.5 | 30.7 | 40.7 | 42.8 | 28.6 | 7.9
2021 | 27.0 | 8.4 | 3.1 | 16.3 | 33.8 | 42.1 | 45.2 | 29.3 | 8.1
2020 | 27.5 | 9.0 | 3.3 | 17.5 | 35.1 | 42.8 | 45.1 | 27.8 | 8.2
2019 | 28.6 | 10.0 | 3.7 | 19.3 | 36.7 | 44.8 | 45.7 | 27.0 | 7.9
2018 | 28.8 | 10.6 | 4.0 | 20.3 | 37.6 | 45.7 | 43.9 | 25.9 | 7.5
2017 | 29.2 | 11.5 | 4.4 | 22.1 | 38.9 | 46.2 | 41.9 | 25.3 | 7.2
2016 | 30.3 | 12.4 | 5.0 | 23.5 | 40.9 | 47.3 | 43.0 | 25.2 | 6.8
Hispanic^5^
2024 | 56.4 | 18.8 | 8.7 | 34.4 | 68.3 | 91.6 | 92.7 | 62.4 | 20.2
2023 | 57.2 | 19.6 | 9.3 | 35.9 | 69.9 | 93.0 | 92.2 | 64.2 | 21.0
2022 | 57.4 | 20.0 | 9.3 | 36.8 | 66.6 | 92.0 | 93.0 | 65.2 | 21.4
2021 | 55.7 | 19.7 | 9.2 | 36.4 | 68.0 | 87.0 | 88.7 | 61.9 | 21.4
2020 | 55.5 | 21.2 | 10.1 | 38.7 | 69.3 | 87.9 | 84.8 | 59.4 | 20.2
2019 | 57.9 | 23.2 | 11.3 | 41.5 | 73.8 | 90.6 | 91.5 | 55.8 | 20.0
2018 | 59.5 | 24.4 | 12.2 | 43.4 | 74.6 | 95.7 | 96.1 | 57.4 | 20.0
2017 | 62.5 | 26.3 | 13.3 | 47.0 | 78.6 | 102.3 | 98.7 | 64.2 | 18.7
2016 | 66.0 | 29.2 | 15.1 | 51.2 | 83.1 | 106.4 | 103.6 | 65.0 | 19.3

^1^Computed by relating total births to unmarried mothers, regardless of age of mother, to unmarried women ages 15–44.

^2^Birth rates computed by relating births to unmarried women age 40 and older to unmarried women ages 40–44; see Technical Notes in this report.

^3^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^4^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

^5^Includes all people of Hispanic origin of any race; see Technical Notes.

NOTES: Rates for 2020 have been revised and may differ from those published in ‘‘Births: Final Data for 2020”; see Technical Notes. For New York, mother's marital status is inferred; see User Guide in reference 8 in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

The birth rate for married women declined by less than 1% in 2024 to 81.3 per 1,000 married females ages 15–44 from 81.6 in 2023. The marital birth rate declined 4% over 2005–2010 but rose 6% from 2010 to 2016 before declining 9% through 2024 (13).

The percentage of all births to unmarried women was 39.5% in 2024, down 1% from 2023 (40.0%) (see Tables 7 and 8 in the 2024 User Guide [8]) (7). The percentage of all births to unmarried women peaked in 2009 at 41.0% (7,13).

Table 8 Timing of prenatal care initiation, by race and Hispanic origin: United States, 2016–2024

Race and Hispanic origin and year | All births | 1st trimester | 2nd trimester | Late or no care | | | Unknown
Race and Hispanic origin and year | All births | 1st trimester | 2nd trimester | Total | 3rd trimester | No care | Unknown
All races and origins^1^ | Number | Percent | | | | | Number
2024 | 3,628,934 | 75.5 | 17.3 | 7.3 | 4.8 | 2.4 | 69,789
2023 | 3,596,017 | 76.1 | 16.9 | 7.0 | 4.7 | 2.3 | 67,433
2022 | 3,667,758 | 77.0 | 16.3 | 6.8 | 4.6 | 2.2 | 79,212
2021 | 3,664,292 | 78.3 | 15.4 | 6.3 | 4.2 | 2.1 | 77,416
2020 | 3,613,647 | 77.7 | 16.1 | 6.2 | 4.3 | 1.9 | 73,968
2019 | 3,747,540 | 77.6 | 16.0 | 6.4 | 4.5 | 1.8 | 84,788
2018 | 3,791,712 | 77.5 | 16.3 | 6.2 | 4.5 | 1.7 | 95,362
2017 | 3,855,500 | 77.3 | 16.5 | 6.3 | 4.5 | 1.8 | 98,417
2016 | 3,945,875 | 77.1 | 16.7 | 6.2 | 4.6 | 1.6 | 113,091
Non-Hispanic, single race^2^
American Indian and Alaska Native:
2024 | 24,021 | 64.0 | 23.1 | 12.9 | 8.4 | 4.5 | 659
2023 | 24,571 | 64.5 | 22.9 | 12.6 | 8.3 | 4.3 | 615
2022 | 25,721 | 64.8 | 22.7 | 12.6 | 8.5 | 4.1 | 760
2021 | 26,124 | 65.8 | 21.7 | 12.5 | 8.2 | 4.3 | 737
2020 | 26,813 | 64.0 | 22.9 | 13.1 | 9.3 | 3.8 | 721
2019 | 28,450 | 63.7 | 23.3 | 13.0 | 8.8 | 4.2 | 694
2018 | 29,092 | 62.6 | 24.3 | 13.1 | 9.1 | 4.0 | 870
2017 | 29,957 | 63.4 | 24.0 | 12.6 | 9.0 | 3.6 | 783
2016 | 31,452 | 63.0 | 24.5 | 12.5 | 9.2 | 3.3 | 811
Asian:
2024 | 226,860 | 80.8 | 13.9 | 5.3 | 4.1 | 1.3 | 5,266
2023 | 215,738 | 81.1 | 14.0 | 4.9 | 3.7 | 1.2 | 4,456
2022 | 218,994 | 82.1 | 13.4 | 4.5 | 3.4 | 1.1 | 4,882
2021 | 213,813 | 83.5 | 12.4 | 4.1 | 3.0 | 1.1 | 4,581
2020 | 219,068 | 82.4 | 13.4 | 4.3 | 3.3 | 1.0 | 4,262
2019 | 238,769 | 82.1 | 12.9 | 5.0 | 4.1 | 0.9 | 4,821
2018 | 240,798 | 81.8 | 13.3 | 4.9 | 4.0 | 0.8 | 4,989
2017 | 249,250 | 81.1 | 13.8 | 5.1 | 4.3 | 0.8 | 5,317
2016 | 254,471 | 80.6 | 14.0 | 5.4 | 4.6 | 0.8 | 6,171
Black:
2024 | 473,377 | 65.1 | 24.0 | 10.9 | 6.8 | 4.1 | 11,004
2023 | 491,494 | 66.3 | 23.3 | 10.4 | 6.6 | 3.8 | 11,749
2022 | 511,439 | 67.6 | 22.4 | 10.0 | 6.3 | 3.7 | 13,972
2021 | 517,889 | 69.7 | 21.1 | 9.1 | 5.6 | 3.5 | 13,434
2020 | 529,811 | 68.4 | 22.6 | 9.1 | 5.8 | 3.3 | 14,544
2019 | 548,075 | 67.6 | 22.8 | 9.6 | 6.4 | 3.2 | 18,209
2018 | 552,029 | 67.1 | 23.0 | 9.9 | 6.8 | 3.1 | 21,500
2017 | 560,715 | 66.6 | 23.2 | 10.2 | 6.9 | 3.3 | 22,710
2016 | 558,622 | 66.5 | 23.5 | 10.0 | 7.0 | 3.0 | 27,400
Native Hawaiian and Other Pacific Islander:
2024 | 10,375 | 47.6 | 29.7 | 22.7 | 15.3 | 7.4 | 414
2023 | 10,115 | 48.5 | 29.1 | 22.4 | 15.5 | 6.9 | 353
2022 | 10,122 | 49.7 | 27.9 | 22.4 | 15.5 | 7.0 | 429
2021 | 9,531 | 51.5 | 27.4 | 21.0 | 14.0 | 7.1 | 514
2020 | 9,626 | 51.9 | 28.5 | 19.6 | 13.2 | 6.3 | 443
2019 | 9,770 | 50.0 | 29.5 | 20.5 | 14.6 | 5.9 | 477
2018 | 9,476 | 51.0 | 28.8 | 20.2 | 14.6 | 5.6 | 374
2017 | 9,426 | 52.5 | 27.9 | 19.6 | 14.8 | 4.8 | 417
2016 | 9,342 | 51.9 | 28.9 | 19.2 | 14.2 | 5.0 | 369
White:
2024 | 1,783,156 | 82.1 | 13.0 | 4.8 | 3.3 | 1.6 | 25,209
2023 | 1,787,051 | 82.4 | 12.9 | 4.7 | 3.2 | 1.5 | 24,638
2022 | 1,840,739 | 82.6 | 12.7 | 4.7 | 3.3 | 1.4 | 30,294
2021 | 1,887,656 | 83.2 | 12.2 | 4.6 | 3.1 | 1.4 | 33,310
2020 | 1,843,432 | 82.8 | 12.7 | 4.5 | 3.2 | 1.3 | 29,811
2019 | 1,915,912 | 82.8 | 12.7 | 4.5 | 3.3 | 1.2 | 34,392
2018 | 1,956,413 | 82.5 | 13.1 | 4.5 | 3.3 | 1.1 | 41,224
2017 | 1,992,461 | 82.4 | 13.1 | 4.5 | 3.3 | 1.2 | 42,157
2016 | 2,056,332 | 82.3 | 13.4 | 4.3 | 3.3 | 1.1 | 48,900
Hispanic^3^
2024 | 984,092 | 67.8 | 22.2 | 10.0 | 6.7 | 3.3 | 22,838
2023 | 945,200 | 68.9 | 21.5 | 9.7 | 6.6 | 3.0 | 21,540
2022 | 937,421 | 70.5 | 20.4 | 9.1 | 6.3 | 2.8 | 24,046
2021 | 885,916 | 72.5 | 19.1 | 8.4 | 5.7 | 2.7 | 20,034
2020 | 866,713 | 72.3 | 19.8 | 7.9 | 5.4 | 2.5 | 19,935
2019 | 886,467 | 72.1 | 19.6 | 8.2 | 5.8 | 2.4 | 21,969
2018 | 886,210 | 72.7 | 19.6 | 7.7 | 5.4 | 2.2 | 22,096
2017 | 898,764 | 72.3 | 20.0 | 7.7 | 5.5 | 2.3 | 22,680
2016 | 918,447 | 72.0 | 20.3 | 7.7 | 5.6 | 2.1 | 24,949

^1^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^2^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

^3^Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

The percentage of nonmarital births in 2024 decreased from 2023 for Asian (11.5%), Black (68.6%), and White (26.2%) women; no significant change was seen for American Indian and Alaska Native (68.6%), Native Hawaiian and Other Pacific Islander (53.7%), and Hispanic (54.2%) women. The number of nonmarital births declined by less than 1% from 2023 (1,440,031) to 2024 (1,433,976) (7).

## Cigarette Smoking Before and During Pregnancy

Of the women who gave birth in 2024, 2.4% reported smoking cigarettes (tobacco only) at any time while pregnant, a 20% decline from 2023 (3.0%) and down 67% from 2016 (7.2%) (Table C; see also Table 21 in the 2024 User Guide [8]) (7,15). A recent report describes trends in cigarette smoking for 2016 through 2021 (18). Cigarette smoking was most common earlier in pregnancy: 2.3% of women smoked in their first trimester, 2.0% in their second, and 1.9% in their third. Of the 3.0% of women who reported smoking in the 3 months before becoming pregnant, 22.3% quit smoking before pregnancy.

By race and Hispanic origin, 8.6% of American Indian and Alaska Native women reported smoking any time during pregnancy, down 10% from 2023; 3.5% of White women, down 20%; 2.3% of Black women, down 15%; 1.3% of Native Hawaiian and Other Pacific Islander women, down 24%; 0.6% of Hispanic women, down 25%; and 0.1% of Asian women, down 50%. See Table D for levels of smoking during pregnancy and quitting before pregnancy among Hispanic subgroups.

## Medical and Health Services Utilization and Source of Payment for the Delivery

### Use and timing of prenatal care

Among women who gave birth in 2024, 75.5% began prenatal care in the first trimester of pregnancy, down 1% from 76.1% in 2023 and the lowest percentage since comparable national data became available in 2016 (77.1%). Late (beginning in the third trimester) or no prenatal care increased 4% in 2024 to 7.3%, from 7.0% in 2023 and higher than any year since 2016 (Tables C and 8; see also Table 10 in the 2024 User Guide [8]). A recent report details recent trends in timing of prenatal care initiation (19).

Among race and Hispanic-origin groups, prenatal care beginning in the first trimester decreased from 2023 to 2024 for White (from 82.4% to 82.1%), Asian (81.1% to 80.8%), Hispanic (68.9% to 67.8%), and Black (66.3% to 65.1%) women (Tables C and 8). Late or no prenatal care increased for Black (10.4% to 10.9%), Hispanic (9.7% to 10.0%), Asian (4.9% to 5.3%), and White (4.7% to 4.8%) women. Changes in both periods for American Indian and Alaska Native and Native Hawaiian and Other Pacific Islander mothers were not significant. Timing of prenatal care continued to vary by race and Hispanic origin in 2024. First trimester care ranged from 47.6% for Native Hawaiian and Other Pacific Islander women to 82.1% for White women; late or no prenatal care ranged from 4.8% for White women to 22.7% for Native Hawaiian and Other Pacific Islander women (Table 8). See Table D for timing of prenatal care initiation among Hispanic subgroups.

### Method of delivery

#### Cesarean delivery

In 2024, the cesarean delivery rate was 32.4%, up from 2023 (32.3%) and 2% higher than the most recent low in 2019 (31.7%) (Tables C and 9; see also Tables 16–18 in the 2024 User Guide [8]). The cesarean delivery rate peaked in 2009 at 32.9%, after increasing every year since 1996 (20.7%) (13).

Table 9 Births, by method of delivery: United States, 2010–2024, and race and Hispanic origin of mother: United States, 2016–2024

Race and Hispanic origin and year | All births | Vaginal | | Cesarean | | | Not stated | Cesarean | | | Vaginal birth after previous cesarean delivery^7^
Race and Hispanic origin and year | All births | Total^1^ | After previous cesarean | Total^2^ | Primary | Low risk^3^ | Not stated | Total^4^ | Primary^5^ | Low risk^6^ | Vaginal birth after previous cesarean delivery^7^
All races and origins^8^ | Number | | | | | | | Percent
2024 | 3,628,934 | 2,450,519 | 86,761 | 1,173,391 | 700,544 | 328,215 | 5,024 | 32.4 | 22.9 | 26.6 | 15.5
2023 | 3,596,017 | 2,431,500 | 83,392 | 1,161,896 | 692,747 | 323,302 | 2,621 | 32.3 | 22.8 | 26.6 | 15.1
2022 | 3,667,758 | 2,486,963 | 82,284 | 1,178,066 | 696,495 | 320,490 | 2,729 | 32.1 | 22.5 | 26.3 | 14.6
2021 | 3,664,292 | 2,486,856 | 79,555 | 1,174,545 | 691,550 | 316,349 | 2,891 | 32.1 | 22.3 | 26.3 | 14.2
2020 | 3,613,647 | 2,462,904 | 77,776 | 1,148,692 | 666,599 | 310,303 | 2,051 | 31.8 | 21.9 | 25.9 | 13.9
2019 | 3,747,540 | 2,558,882 | 80,140 | 1,186,397 | 683,900 | 314,016 | 2,261 | 31.7 | 21.6 | 25.6 | 13.8
2018 | 3,791,712 | 2,581,992 | 78,842 | 1,208,176 | 693,276 | 319,022 | 1,544 | 31.9 | 21.7 | 25.9 | 13.3
2017 | 3,855,500 | 2,621,010 | 76,301 | 1,232,339 | 710,963 | 325,086 | 2,151 | 32.0 | 21.9 | 26.0 | 12.8
2016 | 3,945,875 | 2,684,803 | 75,244 | 1,258,581 | 728,500 | 329,614 | 2,491 | 31.9 | 21.8 | 25.7 | 12.4
2015 | 3,978,497 | 2,703,504 | --- | 1,272,503 | --- | 331,982 | 2,490 | 32.0 | --- | 25.8 | ---
2014 | 3,988,076 | 2,699,951 | --- | 1,284,551 | --- | 337,086 | 3,574 | 32.2 | --- | 26.0 | ---
2013 | 3,932,181 | 2,642,892 | --- | 1,284,339 | --- | 344,405 | 4,950 | 32.7 | --- | 26.8 | ---
2012 | 3,952,841 | 2,650,744 | --- | 1,296,070 | --- | 355,942 | 6,027 | 32.8 | --- | 27.2 | ---
2011 | 3,953,590 | 2,651,428 | --- | 1,293,267 | --- | 359,669 | 8,895 | 32.8 | --- | 27.2 | ---
2010 | 3,999,386 | 2,680,947 | --- | 1,309,182 | --- | 368,523 | 9,257 | 32.8 | --- | 27.5 | ---
Non-Hispanic, single race^9^
American Indian and Alaska Native:
2024 | 24,021 | 16,842 | 559 | 7,165 | 4,019 | 1,643 | 14 | 29.8 | 19.9 | 24.1 | 15.1
2023 | 24,571 | 17,214 | 609 | 7,348 | 4,046 | 1,609 | 9 | 29.9 | 19.7 | 23.6 | 15.6
2022 | 25,721 | 18,157 | 552 | 7,548 | 4,089 | 1,595 | 16 | 29.4 | 18.9 | 23.0 | 13.8
2021 | 26,124 | 18,499 | 585 | 7,612 | 4,134 | 1,599 | 13 | 29.2 | 18.8 | 23.0 | 14.4
2020 | 26,813 | 19,092 | 635 | 7,716 | 4,083 | 1,715 | 5 | 28.8 | 18.2 | 23.6 | 14.9
2019 | 28,450 | 20,219 | 617 | 8,222 | 4,371 | 1,731 | 9 | 28.9 | 18.3 | 22.8 | 13.8
2018 | 29,092 | 20,744 | 679 | 8,337 | 4,437 | 1,682 | 11 | 28.7 | 18.2 | 22.3 | 14.9
2017 | 29,957 | 21,400 | 655 | 8,544 | 4,497 | 1,771 | 13 | 28.5 | 17.9 | 22.8 | 14.0
2016 | 31,452 | 22,627 | 656 | 8,815 | 4,578 | 1,711 | 10 | 28.0 | 17.3 | 21.2 | 13.4
Asian:
2024 | 226,860 | 148,709 | 5,058 | 77,968 | 49,945 | 27,925 | 183 | 34.4 | 25.8 | 30.1 | 15.3
2023 | 215,738 | 141,868 | 4,786 | 73,782 | 47,068 | 25,961 | 88 | 34.2 | 25.6 | 30.1 | 15.2
2022 | 218,994 | 145,659 | 5,042 | 73,230 | 45,423 | 24,780 | 105 | 33.5 | 24.4 | 29.2 | 15.4
2021 | 213,813 | 142,881 | 4,812 | 70,811 | 43,336 | 23,374 | 121 | 33.1 | 23.9 | 28.4 | 14.9
2020 | 219,068 | 147,540 | 4,861 | 71,457 | 43,294 | 23,952 | 71 | 32.6 | 23.3 | 27.7 | 14.7
2019 | 238,769 | 160,704 | 5,335 | 77,948 | 47,222 | 25,746 | 117 | 32.7 | 23.3 | 27.4 | 14.8
2018 | 240,798 | 161,197 | 4,999 | 79,571 | 47,921 | 26,196 | 30 | 33.0 | 23.5 | 27.6 | 13.6
2017 | 249,250 | 166,337 | 4,972 | 82,850 | 49,773 | 27,309 | 63 | 33.2 | 23.6 | 27.8 | 13.1
2016 | 254,471 | 169,753 | 4,944 | 84,631 | 51,106 | 27,540 | 87 | 33.3 | 23.7 | 27.5 | 12.9
Black:
2024 | 473,377 | 295,431 | 13,044 | 177,138 | 103,876 | 44,938 | 808 | 37.5 | 26.9 | 31.5 | 15.1
2023 | 491,494 | 309,644 | 13,304 | 181,602 | 105,603 | 44,791 | 248 | 37.0 | 26.3 | 30.8 | 14.9
2022 | 511,439 | 323,076 | 13,430 | 188,132 | 109,189 | 46,477 | 231 | 36.8 | 26.1 | 30.8 | 14.6
2021 | 517,889 | 327,049 | 12,687 | 190,500 | 111,166 | 47,977 | 340 | 36.8 | 26.2 | 31.2 | 13.8
2020 | 529,811 | 337,264 | 12,911 | 192,338 | 110,612 | 48,448 | 209 | 36.3 | 25.5 | 30.6 | 13.7
2019 | 548,075 | 351,191 | 13,159 | 196,672 | 113,001 | 48,481 | 212 | 35.9 | 25.1 | 30.0 | 13.6
2018 | 552,029 | 352,750 | 12,702 | 199,117 | 114,150 | 49,481 | 162 | 36.1 | 25.2 | 30.3 | 13.0
2017 | 560,715 | 358,467 | 12,457 | 201,991 | 117,054 | 50,217 | 257 | 36.0 | 25.3 | 30.4 | 12.8
2016 | 558,622 | 357,859 | 11,763 | 200,460 | 117,410 | 50,287 | 303 | 35.9 | 25.4 | 30.3 | 12.4
Native Hawaiian and OtherPacific Islander:
2024 | 10,375 | 6,937 | 476 | 3,434 | 1,903 | 719 | 4 | 33.1 | 22.8 | 29.0 | 23.8
2023 | 10,115 | 6,825 | 429 | 3,280 | 1,812 | 697 | 10 | 32.5 | 22.1 | 28.9 | 22.6
2022 | 10,122 | 6,831 | 372 | 3,280 | 1,863 | 759 | 11 | 32.4 | 22.4 | 30.1 | 20.8
2021 | 9,531 | 6,430 | 355 | 3,094 | 1,769 | 656 | 7 | 32.5 | 22.6 | 29.8 | 21.2
2020 | 9,626 | 6,514 | 332 | 3,107 | 1,753 | 733 | 5 | 32.3 | 22.1 | 29.2 | 19.7
2019 | 9,770 | 6,812 | 358 | 2,954 | 1,588 | 647 | 4 | 30.2 | 19.8 | 26.1 | 20.8
2018 | 9,476 | 6,527 | 324 | 2,946 | 1,602 | 615 | 3 | 31.1 | 20.5 | 26.5 | 19.4
2017 | 9,426 | 6,504 | 310 | 2,921 | 1,580 | 625 | 1 | 31.0 | 20.3 | 26.8 | 18.8
2016 | 9,342 | 6,495 | 345 | 2,845 | 1,528 | 604 | 2 | 30.5 | 19.9 | 26.7 | 20.8
White:
2024 | 1,783,156 | 1,228,287 | 40,015 | 552,734 | 338,234 | 156,845 | 2,135 | 31.0 | 22.2 | 25.5 | 15.8
2023 | 1,787,051 | 1,229,961 | 38,631 | 555,949 | 340,939 | 159,184 | 1,141 | 31.1 | 22.3 | 25.6 | 15.3
2022 | 1,840,739 | 1,268,223 | 38,353 | 571,371 | 347,632 | 160,403 | 1,145 | 31.1 | 22.1 | 25.3 | 14.7
2021 | 1,887,656 | 1,301,124 | 38,908 | 585,346 | 353,971 | 161,487 | 1,186 | 31.0 | 21.9 | 25.2 | 14.4
2020 | 1,843,432 | 1,275,917 | 36,967 | 566,811 | 339,770 | 157,635 | 704 | 30.8 | 21.5 | 24.9 | 14.0
2019 | 1,915,912 | 1,327,934 | 38,442 | 587,111 | 348,616 | 160,622 | 867 | 30.7 | 21.3 | 24.7 | 13.9
2018 | 1,956,413 | 1,353,424 | 38,345 | 602,361 | 356,796 | 164,087 | 628 | 30.8 | 21.4 | 24.9 | 13.5
2017 | 1,992,461 | 1,375,702 | 37,295 | 615,830 | 366,505 | 167,434 | 929 | 30.9 | 21.5 | 24.9 | 13.0
2016 | 2,056,332 | 1,419,788 | 37,442 | 635,588 | 379,240 | 172,006 | 956 | 30.9 | 21.5 | 24.7 | 12.8
Hispanic^10^
2024 | 984,092 | 667,029 | 24,553 | 316,017 | 178,669 | 84,817 | 1,046 | 32.1 | 21.8 | 25.9 | 15.2
2023 | 945,200 | 642,354 | 22,688 | 302,522 | 170,279 | 80,106 | 324 | 32.0 | 21.6 | 25.9 | 14.7
2022 | 937,421 | 640,248 | 21,880 | 296,706 | 165,122 | 75,640 | 467 | 31.7 | 21.1 | 25.6 | 14.3
2021 | 885,916 | 605,819 | 19,485 | 279,607 | 154,162 | 70,443 | 490 | 31.6 | 20.8 | 25.5 | 13.5
2020 | 866,713 | 594,463 | 19,469 | 271,865 | 145,786 | 67,517 | 385 | 31.4 | 20.2 | 25.1 | 13.4
2019 | 886,467 | 608,445 | 19,612 | 277,578 | 147,597 | 66,705 | 444 | 31.3 | 20.1 | 24.8 | 13.1
2018 | 886,210 | 605,674 | 19,371 | 280,386 | 147,149 | 67,040 | 150 | 31.6 | 20.1 | 25.4 | 12.7
2017 | 898,764 | 613,101 | 18,423 | 285,379 | 150,592 | 67,860 | 284 | 31.8 | 20.2 | 25.6 | 12.0
2016 | 918,447 | 627,095 | 17,847 | 290,832 | 153,462 | 67,278 | 520 | 31.7 | 20.1 | 25.1 | 11.5

--- Comparable data not available for the 50 states and District of Columbia for 2010–2015 because not all reporting areas had adopted the 2003 revised U.S. Certificate of Live Birth.

^1^Includes unknown type of vaginal delivery; see User Guide in reference 8 in this report.

^2^Includes unknown type of cesarean delivery; see User Guide in reference 8.

^3^Singleton, term (37 completed weeks of gestation or more based on the obstetric estimate), cephalic (head first), cesarean deliveries to women having a first birth.

^4^Percentage of all live births delivered by cesarean.

^5^Rate is number of births to women having a cesarean delivery per 100 births to women without a previous cesarean.

^6^Rate is number of singleton, term (37 completed weeks of gestation or more based on the obstetric estimate), cephalic, cesarean deliveries to women having a first birth per 100 women delivering singleton, term, cephalic first births.

^7^Rate is number of births to women having a vaginal delivery per 100 births to women with a previous cesarean delivery.

^8^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^9^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

^10^Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

The cesarean delivery rate increased in 2024 for Black (37.5% from 37.0% in 2023) and Hispanic (32.1% from 32.0%) women and decreased for White (31.0% from 31.1%) women; changes for American Indian and Alaska Native, Asian, and Native Hawaiian and Other Pacific Islander women were not significant. Black women continued to have the highest cesarean delivery rate in 2024. See Table D for cesarean delivery among Hispanic subgroups.

Low-risk cesarean delivery—The low-risk cesarean delivery rate was unchanged in 2024 at 26.6%. The low-risk cesarean delivery rate is cesarean delivery among nulliparous (first birth), term (37 completed weeks or more based on the obstetric estimate), singleton (one fetus), and cephalic (head first) births. See Tables C, D, and 9 in this report and Tables 16 and 18 in the 2024 User Guide (8) for details by age and race and Hispanic origin of the mother.

Primary cesarean delivery—In 2024, the primary cesarean delivery rate, which measures cesarean deliveries among women who have not had a previous cesarean delivery, was 22.9%, up from 22.8% in 2023 (Table 9; see also Table 18 in the 2024 User Guide [8]). An earlier report describes trends in primary and repeat cesarean delivery through 2021 (20).

Vaginal birth after previous cesarean delivery—The rate of vaginal birth after previous cesarean delivery measures vaginal births among women with a previous cesarean delivery. In 2024, 15.5% of women with a previous cesarean delivered vaginally, up 3% from 15.1% in 2023. The rate has increased every year since 2016, when comparable national data became available (Table 9; see also Table 18 in the 2024 User Guide [8]).

### Source of payment for the delivery

The principal sources of payment for the delivery of most births in 2024 continued to be private insurance followed by Medicaid. The percentage of births covered by private insurance increased from 2023 to 2024 (51.0% to 51.8%), while the percentage of births covered by Medicaid declined (41.5% to 40.2%). The percentage of births in the category self-pay, generally considered to indicate uninsured deliveries, increased from 2023 to 2024 (4.4% to 4.7%). The remainder of births were covered by other insurance (3.3%, up from 3.2% in 2023), which includes Indian Health Service, CHAMPUS or TRICARE, other government (federal, state, or local), or charity (Table C; see also Table 19 in the 2024 User Guide [8]) (7). Private insurance has been the most common principal source of payment since national data became available in 2016 (15). An earlier report describes source of payment for the delivery by various maternal characteristics for 2021 (21).

The percentage of births covered by private insurance increased for nearly all race and Hispanic origin groups: American Indian and Alaska Native (from 23.7% to 24.6%), Asian (72.4% to 72.8%), Black (30.4% to 32.0%), White (65.1% to 65.9%), and Hispanic (31.5% to 32.3%) women from 2023 to 2024; the percentage was essentially unchanged for Native Hawaiian and Other Pacific Islander women (28.0% to 28.6%) (7). The percentage of births covered by Medicaid declined for most groups from 2023 to 2024: American Indian and Alaska Native (from 65.3% to 63.2%), Asian (22.1% to 21.3%), Black (64.5% to 62.4%), Hispanic (58.8% to 57.3%), and White (27.6% to 26.6%) women, but it was essentially unchanged for Native Hawaiian and Other Pacific Islander women (59.5% to 58.3%). See Table D for source of payment coverage among Hispanic subgroups.

## Infant Health Characteristics

### Period of gestation

The U.S. preterm birth rate was unchanged from 2023 to 2024 at 10.41%. The preterm birth rate (percentage of all births delivered at less than 37 completed weeks of gestation) declined steadily from 2007 (10.44%) to 2014 (9.57%) (13), rose 7% through 2019 (10.23%), fluctuated from 2019 to 2022, and has been essentially stable since (Tables C and 10; see also Tables 25–27 in the 2024 User Guide [8]). (National data based on the obstetric estimate of gestation are available only from 2007 [22]; see Technical Notes.)

Table 10 Births, by gestational age in weeks: United States, 2010–2024, and race and Hispanic origin of mother: United States, 2016–2024

Race and Hispanic origin of mother and year | All births | Preterm^1^ | | | | | | Term^1^ | | | | | Post term^1^ | Not stated
Race and Hispanic origin of mother and year | All births | Total under 37 | Total under 34 | Early | | | Late | Total 37–41 | Early | Full | Late | | 42 and over | Not stated
Race and Hispanic origin of mother and year | All births | Total under 37 | Total under 34 | Under 28 | 28–31 | 32–33 | 34–36 | Total 37–41 | 37–38 | 39–40 | 41 | | 42 and over | Not stated
All races and origins^2^ | Number | Percent | | | | | | | | | | | | Number
2024 | 3,628,934 | 10.41 | 2.72 | 0.63 | 0.91 | 1.19 | 7.69 | 89.34 | 30.26 | 54.61 | 4.47 | | 0.25 | 4,457
2023 | 3,596,017 | 10.41 | 2.76 | 0.64 | 0.92 | 1.20 | 7.64 | 89.34 | 29.84 | 54.94 | 4.56 | | 0.26 | 2,642
2022 | 3,667,758 | 10.38 | 2.76 | 0.64 | 0.92 | 1.20 | 7.62 | 89.36 | 29.31 | 55.32 | 4.73 | | 0.26 | 2,671
2021 | 3,664,292 | 10.49 | 2.81 | 0.64 | 0.95 | 1.22 | 7.67 | 89.27 | 28.76 | 55.90 | 4.61 | | 0.25 | 2,992
2020 | 3,613,647 | 10.09 | 2.70 | 0.64 | 0.90 | 1.15 | 7.40 | 89.66 | 27.78 | 57.00 | 4.88 | | 0.25 | 2,478
2019 | 3,747,540 | 10.23 | 2.77 | 0.66 | 0.93 | 1.18 | 7.46 | 89.52 | 27.31 | 57.02 | 5.19 | | 0.25 | 2,406
2018 | 3,791,712 | 10.02 | 2.75 | 0.66 | 0.91 | 1.18 | 7.28 | 89.68 | 26.53 | 57.24 | 5.90 | | 0.30 | 2,507
2017 | 3,855,500 | 9.93 | 2.76 | 0.67 | 0.92 | 1.17 | 7.17 | 89.74 | 26.00 | 57.49 | 6.25 | | 0.33 | 2,759
2016 | 3,945,875 | 9.85 | 2.76 | 0.68 | 0.92 | 1.17 | 7.09 | 89.80 | 25.47 | 57.94 | 6.38 | | 0.35 | 3,454
2015 | 3,978,497 | 9.63 | 2.76 | 0.68 | 0.91 | 1.17 | 6.87 | 89.98 | 24.99 | 58.47 | 6.51 | | 0.40 | 2,926
2014 | 3,988,076 | 9.57 | 2.75 | 0.69 | 0.91 | 1.15 | 6.82 | 90.43 | 24.76 | 58.72 | 6.53 | | 0.42 | 3,246
2013 | 3,932,181 | 9.62 | 2.79 | 0.70 | 0.92 | 1.17 | 6.83 | 90.38 | 24.81 | 58.85 | 6.31 | | 0.41 | 7,467
2012 | 3,952,841 | 9.76 | 2.80 | 0.71 | 0.92 | 1.17 | 6.96 | 90.24 | 25.47 | 58.30 | 6.06 | | 0.40 | 8,380
2011 | 3,953,590 | 9.81 | 2.81 | 0.70 | 0.93 | 1.18 | 6.99 | 90.19 | 26.09 | 57.51 | 6.16 | | 0.43 | 9,290
2010 | 3,999,386 | 9.98 | 2.84 | 0.71 | 0.94 | 1.18 | 7.15 | 90.01 | 27.29 | 56.08 | 6.19 | | 0.46 | 10,538
Non-Hispanic, single race^3^
American Indian and Alaska Native:
2024 | 24,021 | 12.64 | 3.39 | 0.72 | 1.06 | 1.61 | 9.25 | 87.10 | 33.21 | 50.35 | 3.54 | | 0.25 | 52
2023 | 24,571 | 12.23 | 3.02 | 0.71 | 1.02 | 1.30 | 9.21 | 87.57 | 33.36 | 50.45 | 3.76 | | 0.20 | 48
2022 | 25,721 | 12.61 | 3.28 | 0.74 | 1.11 | 1.43 | 9.33 | 87.08 | 31.66 | 51.43 | 3.99 | | 0.31 | 60
2021 | 26,124 | 12.26 | 3.08 | 0.62 | 0.95 | 1.50 | 9.18 | 87.49 | 31.56 | 52.09 | 3.84 | | 0.25 | 50
2020 | 26,813 | 11.61 | 3.05 | 0.66 | 0.97 | 1.42 | 8.56 | 88.17 | 31.09 | 52.88 | 4.21 | | 0.21 | 43
2019 | 28,450 | 11.59 | 2.90 | 0.57 | 1.00 | 1.33 | 8.69 | 88.15 | 30.41 | 53.31 | 4.44 | | 0.26 | 46
2018 | 29,092 | 11.52 | 3.17 | 0.62 | 1.05 | 1.49 | 8.35 | 88.20 | 30.00 | 53.32 | 4.87 | | 0.29 | 66
2017 | 29,957 | 11.86 | 3.09 | 0.71 | 1.02 | 1.36 | 8.77 | 87.88 | 28.86 | 53.71 | 5.30 | | 0.27 | 59
2016 | 31,452 | 11.39 | 2.98 | 0.72 | 1.02 | 1.24 | 8.41 | 88.24 | 28.52 | 53.90 | 5.82 | | 0.37 | 57
Asian:
2024 | 226,860 | 9.16 | 2.30 | 0.52 | 0.78 | 1.00 | 6.85 | 90.78 | 32.06 | 55.67 | 3.06 | | 0.06 | 147
2023 | 215,738 | 9.08 | 2.29 | 0.50 | 0.78 | 1.01 | 6.79 | 90.85 | 31.74 | 55.90 | 3.22 | | 0.06 | 54
2022 | 218,994 | 9.19 | 2.25 | 0.47 | 0.77 | 1.01 | 6.95 | 90.72 | 31.61 | 55.75 | 3.36 | | 0.09 | 54
2021 | 213,813 | 9.23 | 2.33 | 0.50 | 0.81 | 1.03 | 6.90 | 90.69 | 30.91 | 56.45 | 3.33 | | 0.08 | 66
2020 | 219,068 | 8.51 | 2.08 | 0.44 | 0.69 | 0.95 | 6.43 | 91.42 | 29.61 | 58.05 | 3.76 | | 0.07 | 36
2019 | 238,769 | 8.72 | 2.13 | 0.47 | 0.74 | 0.92 | 6.59 | 91.18 | 29.03 | 58.02 | 4.13 | | 0.10 | 51
2018 | 240,798 | 8.57 | 2.11 | 0.47 | 0.72 | 0.92 | 6.46 | 91.30 | 28.53 | 58.07 | 4.69 | | 0.13 | 57
2017 | 249,250 | 8.53 | 2.19 | 0.50 | 0.70 | 0.99 | 6.34 | 91.33 | 28.09 | 58.25 | 4.99 | | 0.15 | 67
2016 | 254,471 | 8.63 | 2.13 | 0.45 | 0.74 | 0.94 | 6.50 | 91.20 | 27.91 | 58.12 | 5.17 | | 0.17 | 134
Black:
2024 | 473,377 | 14.86 | 4.85 | 1.43 | 1.58 | 1.83 | 10.01 | 84.93 | 33.86 | 47.71 | 3.37 | | 0.21 | 721
2023 | 491,494 | 14.65 | 4.86 | 1.43 | 1.61 | 1.82 | 9.79 | 85.14 | 33.47 | 48.26 | 3.42 | | 0.21 | 298
2022 | 511,439 | 14.59 | 4.89 | 1.47 | 1.56 | 1.86 | 9.70 | 85.18 | 32.73 | 48.81 | 3.65 | | 0.23 | 326
2021 | 517,889 | 14.75 | 4.95 | 1.44 | 1.67 | 1.85 | 9.80 | 85.04 | 32.27 | 49.28 | 3.49 | | 0.21 | 391
2020 | 529,811 | 14.36 | 4.82 | 1.47 | 1.58 | 1.77 | 9.54 | 85.43 | 31.22 | 50.47 | 3.74 | | 0.21 | 300
2019 | 548,075 | 14.39 | 4.94 | 1.52 | 1.63 | 1.79 | 9.45 | 85.39 | 30.40 | 50.93 | 4.06 | | 0.21 | 326
2018 | 552,029 | 14.13 | 4.90 | 1.51 | 1.60 | 1.79 | 9.23 | 85.62 | 29.64 | 51.34 | 4.64 | | 0.25 | 384
2017 | 560,715 | 13.93 | 4.87 | 1.53 | 1.62 | 1.72 | 9.06 | 85.79 | 28.93 | 51.90 | 4.96 | | 0.28 | 445
2016 | 558,622 | 13.77 | 4.93 | 1.56 | 1.61 | 1.75 | 8.84 | 85.94 | 28.48 | 52.42 | 5.04 | | 0.30 | 506
Native Hawaiian and OtherPacific Islander:
2024 | 10,375 | 12.54 | 3.47 | 0.74 | 1.07 | 1.65 | 9.08 | 87.21 | 32.17 | 50.58 | 4.45 | | 0.25 | 19
2023 | 10,115 | 12.52 | 3.24 | 0.83 | 0.99 | 1.42 | 9.28 | 87.22 | 31.31 | 51.62 | 4.28 | | 0.27 | 17
2022 | 10,122 | 11.96 | 3.06 | 0.57 | 1.09 | 1.40 | 8.90 | 87.65 | 30.45 | 51.88 | 5.33 | | 0.39 | 23
2021 | 9,531 | 12.69 | 3.55 | 0.83 | 1.17 | 1.56 | 9.14 | 87.01 | 30.11 | 52.52 | 4.38 | | 0.29 | 21
2020 | 9,626 | 12.05 | 3.08 | 0.75 | 1.02 | 1.31 | 8.97 | 87.64 | 30.06 | 52.20 | 5.38 | | 0.31 | 13
2019 | 9,770 | 11.15 | 2.90 | 0.84 | 0.82 | 1.24 | 8.25 | 88.61 | 29.57 | 53.79 | 5.25 | | 0.24 | 15
2018 | 9,476 | 11.79 | 3.59 | 0.76 | 1.26 | 1.57 | 8.20 | 87.85 | 28.26 | 53.96 | 5.63 | | 0.36 | 13
2017 | 9,426 | 10.54 | 2.68 | 0.54 | 0.84 | 1.30 | 7.86 | 89.01 | 28.66 | 53.67 | 6.68 | | 0.45 | 16
2016 | 9,342 | 11.52 | 3.12 | 0.72 | 1.10 | 1.30 | 8.40 | 88.08 | 27.43 | 54.38 | 6.26 | | 0.40 | 14
White:
2024 | 1,783,156 | 9.49 | 2.26 | 0.43 | 0.75 | 1.08 | 7.22 | 90.18 | 28.75 | 56.28 | 5.14 | | 0.34 | 1,783
2023 | 1,787,051 | 9.44 | 2.28 | 0.44 | 0.76 | 1.09 | 7.16 | 90.22 | 28.30 | 56.72 | 5.20 | | 0.34 | 911
2022 | 1,840,739 | 9.44 | 2.28 | 0.43 | 0.76 | 1.08 | 7.16 | 90.24 | 27.68 | 57.25 | 5.31 | | 0.32 | 1,011
2021 | 1,887,656 | 9.50 | 2.31 | 0.44 | 0.77 | 1.10 | 7.18 | 90.19 | 27.04 | 57.93 | 5.23 | | 0.31 | 1,215
2020 | 1,843,432 | 9.10 | 2.21 | 0.44 | 0.74 | 1.03 | 6.90 | 90.58 | 25.98 | 59.08 | 5.53 | | 0.32 | 1,001
2019 | 1,915,912 | 9.26 | 2.27 | 0.44 | 0.77 | 1.06 | 6.99 | 90.42 | 25.56 | 59.01 | 5.84 | | 0.32 | 924
2018 | 1,956,413 | 9.09 | 2.26 | 0.44 | 0.76 | 1.07 | 6.83 | 90.53 | 24.68 | 59.16 | 6.70 | | 0.37 | 924
2017 | 1,992,461 | 9.05 | 2.30 | 0.46 | 0.77 | 1.06 | 6.76 | 90.54 | 24.16 | 59.27 | 7.11 | | 0.40 | 1,051
2016 | 2,056,332 | 9.04 | 2.33 | 0.48 | 0.78 | 1.07 | 6.72 | 90.53 | 23.64 | 59.61 | 7.28 | | 0.43 | 1,409
Hispanic^4^
2024 | 984,092 | 10.07 | 2.56 | 0.61 | 0.87 | 1.07 | 7.51 | 89.78 | 30.84 | 54.88 | 4.06 | | 0.15 | 891
2023 | 945,200 | 10.14 | 2.62 | 0.63 | 0.88 | 1.10 | 7.52 | 89.69 | 30.40 | 55.11 | 4.18 | | 0.17 | 447
2022 | 937,421 | 10.06 | 2.60 | 0.60 | 0.88 | 1.12 | 7.46 | 89.77 | 30.10 | 55.24 | 4.42 | | 0.17 | 421
2021 | 885,916 | 10.23 | 2.67 | 0.63 | 0.91 | 1.14 | 7.57 | 89.62 | 29.83 | 55.62 | 4.17 | | 0.15 | 496
2020 | 866,713 | 9.84 | 2.52 | 0.60 | 0.84 | 1.07 | 7.32 | 90.01 | 29.00 | 56.61 | 4.41 | | 0.15 | 348
2019 | 886,467 | 9.97 | 2.61 | 0.63 | 0.87 | 1.11 | 7.36 | 89.87 | 28.66 | 56.52 | 4.68 | | 0.16 | 344
2018 | 886,210 | 9.73 | 2.56 | 0.62 | 0.84 | 1.09 | 7.17 | 90.07 | 28.05 | 56.83 | 5.19 | | 0.20 | 382
2017 | 898,764 | 9.62 | 2.56 | 0.62 | 0.85 | 1.09 | 7.05 | 90.16 | 27.58 | 57.15 | 5.43 | | 0.23 | 455
2016 | 918,447 | 9.45 | 2.98 | 0.62 | 0.84 | 1.08 | 6.92 | 90.30 | 27.02 | 57.85 | 5.43 | | 0.25 | 676
All races and origins^2^ | Number
2024 | 3,628,934 | 377,204 | 98,629 | 22,774 | 32,893 | 42,962 | 278,575 | 3,238,129 | 1,096,713 | 1,979,343 | 162,073 | | 9,144 | 4,457
2023 | 3,596,017 | 373,902 | 99,255 | 23,096 | 33,153 | 43,006 | 274,647 | 3,210,174 | 1,072,092 | 1,974,300 | 163,782 | | 9,299 | 2,642
2022 | 3,667,758 | 380,548 | 101,167 | 23,369 | 33,663 | 44,135 | 279,381 | 3,275,078 | 1,074,082 | 2,027,670 | 173,326 | | 9,461 | 2,671
2021 | 3,664,292 | 383,979 | 103,004 | 23,527 | 34,731 | 44,746 | 280,975 | 3,268,342 | 1,052,935 | 2,046,786 | 168,621 | | 8,979 | 2,992
2020 | 3,613,647 | 364,487 | 97,420 | 23,286 | 32,463 | 41,671 | 267,067 | 3,237,819 | 1,003,260 | 2,058,396 | 176,163 | | 8,863 | 2,478
2019 | 3,747,540 | 383,061 | 103,759 | 24,758 | 34,748 | 44,253 | 279,302 | 3,352,638 | 1,022,874 | 2,135,518 | 194,246 | | 9,435 | 2,406
2018 | 3,791,712 | 379,777 | 104,031 | 24,945 | 34,386 | 44,700 | 275,746 | 3,398,110 | 1,005,405 | 2,169,016 | 223,689 | | 11,318 | 2,507
2017 | 3,855,500 | 382,726 | 106,417 | 25,913 | 35,476 | 45,028 | 276,309 | 3,457,455 | 1,001,601 | 2,214,983 | 240,871 | | 12,560 | 2,759
2016 | 3,945,875 | 388,218 | 108,836 | 26,618 | 36,239 | 45,979 | 279,382 | 3,540,290 | 1,004,224 | 2,284,399 | 251,667 | | 13,913 | 3,454
2015 | 3,978,497 | 382,786 | 109,660 | 26,996 | 36,149 | 46,515 | 273,126 | 3,577,072 | 993,599 | 2,324,474 | 258,999 | | 15,713 | 2,926
2014 | 3,988,076 | 381,321 | 109,474 | 27,320 | 36,245 | 45,909 | 271,847 | 3,586,933 | 986,745 | 2,339,796 | 260,392 | | 19,822 | 3,246
2013 | 3,932,181 | 377,655 | 109,435 | 27,550 | 36,096 | 45,789 | 268,220 | 3,283,457 | 973,569 | 2,309,888 | 247,476 | | 16,126 | 7,467
2012 | 3,952,841 | 385,082 | 110,444 | 28,004 | 36,366 | 46,074 | 274,638 | 3,304,365 | 1,004,750 | 2,299,615 | 239,148 | | 15,866 | 8,380
2011 | 3,953,590 | 386,855 | 111,002 | 27,737 | 36,758 | 46,507 | 275,853 | 3,297,649 | 1,029,157 | 2,268,492 | 242,999 | | 16,797 | 9,290
2010 | 3,999,386 | 398,402 | 113,131 | 28,437 | 37,435 | 47,259 | 285,271 | 3,325,476 | 1,088,564 | 2,236,912 | 246,768 | | 18,413 | 10,538
Non-Hispanic, single race^3^
American Indian and Alaska Native:
2024 | 24,021 | 3,030 | 812 | 172 | 254 | 386 | 2,218 | 20,878 | 7,960 | 12,069 | 849 | | 61 | 52
2023 | 24,571 | 3,000 | 741 | 173 | 250 | 318 | 2,259 | 21,474 | 8,181 | 12,372 | 921 | | 49 | 48
2022 | 25,721 | 3,235 | 842 | 190 | 284 | 368 | 2,393 | 22,346 | 8,124 | 13,198 | 1,024 | | 80 | 60
2021 | 26,124 | 3,196 | 802 | 162 | 249 | 391 | 2,394 | 22,813 | 8,230 | 13,581 | 1,002 | | 65 | 50
2020 | 26,813 | 3,109 | 817 | 177 | 261 | 379 | 2,292 | 23,604 | 8,322 | 14,155 | 1,127 | | 57 | 43
2019 | 28,450 | 3,292 | 824 | 162 | 284 | 378 | 2,468 | 25,039 | 8,637 | 15,142 | 1,260 | | 73 | 46
2018 | 29,092 | 3,343 | 919 | 180 | 306 | 433 | 2,424 | 25,600 | 8,709 | 15,478 | 1,413 | | 83 | 66
2017 | 29,957 | 3,545 | 923 | 213 | 304 | 406 | 2,622 | 26,273 | 8,629 | 16,059 | 1,585 | | 80 | 59
2016 | 31,452 | 3,577 | 936 | 227 | 321 | 388 | 2,641 | 27,702 | 8,954 | 16,921 | 1,827 | | 116 | 57
Asian:
2024 | 226,860 | 20,764 | 5,223 | 1,184 | 1,778 | 2,261 | 15,541 | 205,810 | 72,673 | 126,204 | 6,933 | | 139 | 147
2023 | 215,738 | 19,587 | 4,938 | 1,081 | 1,672 | 2,185 | 14,649 | 195,957 | 68,461 | 120,557 | 6,939 | | 140 | 54
2022 | 218,994 | 20,127 | 4,920 | 1,029 | 1,676 | 2,215 | 15,207 | 198,619 | 69,213 | 122,060 | 7,346 | | 194 | 54
2021 | 213,813 | 19,719 | 4,981 | 1,063 | 1,724 | 2,194 | 14,738 | 193,854 | 66,074 | 120,653 | 7,127 | | 174 | 66
2020 | 219,068 | 18,632 | 4,556 | 960 | 1,517 | 2,079 | 14,076 | 200,237 | 64,857 | 127,141 | 8,239 | | 163 | 36
2019 | 238,769 | 20,817 | 5,092 | 1,118 | 1,766 | 2,208 | 15,725 | 217,663 | 69,306 | 138,503 | 9,854 | | 238 | 51
2018 | 240,798 | 20,629 | 5,089 | 1,124 | 1,739 | 2,226 | 15,540 | 219,793 | 68,689 | 139,802 | 11,302 | | 319 | 57
2017 | 249,250 | 21,250 | 5,453 | 1,246 | 1,751 | 2,456 | 15,797 | 227,567 | 69,989 | 145,139 | 12,439 | | 366 | 67
2016 | 254,471 | 21,952 | 5,420 | 1,139 | 1,890 | 2,391 | 16,532 | 231,949 | 70,990 | 147,811 | 13,148 | | 436 | 134
Black:
2024 | 473,377 | 70,231 | 22,913 | 6,773 | 7,485 | 8,655 | 47,318 | 401,430 | 160,042 | 225,481 | 15,907 | | 995 | 721
2023 | 491,494 | 71,956 | 23,859 | 7,046 | 7,887 | 8,926 | 48,097 | 418,212 | 164,390 | 237,042 | 16,780 | | 1,028 | 298
2022 | 511,439 | 74,553 | 24,986 | 7,496 | 7,984 | 9,506 | 49,567 | 435,385 | 167,263 | 249,451 | 18,671 | | 1,175 | 326
2021 | 517,889 | 76,334 | 25,641 | 7,445 | 8,640 | 9,556 | 50,693 | 440,079 | 167,006 | 255,016 | 18,057 | | 1,085 | 391
2020 | 529,811 | 76,059 | 25,537 | 7,802 | 8,381 | 9,354 | 50,522 | 452,357 | 165,321 | 267,237 | 19,799 | | 1,095 | 300
2019 | 548,075 | 78,829 | 27,063 | 8,332 | 8,927 | 9,804 | 51,766 | 467,745 | 166,528 | 278,956 | 22,261 | | 1,175 | 326
2018 | 552,029 | 77,939 | 27,008 | 8,348 | 8,804 | 9,856 | 50,931 | 472,316 | 163,530 | 283,202 | 25,584 | | 1,390 | 384
2017 | 560,715 | 78,024 | 27,274 | 8,548 | 9,070 | 9,656 | 50,750 | 480,661 | 162,072 | 290,803 | 27,786 | | 1,585 | 445
2016 | 558,622 | 76,834 | 27,501 | 8,729 | 8,987 | 9,785 | 49,333 | 479,630 | 158,937 | 292,539 | 28,154 | | 1,652 | 506
Native Hawaiian and OtherPacific Islander:
2024 | 10,375 | 1,299 | 359 | 77 | 111 | 171 | 940 | 9,031 | 3,332 | 5,238 | 461 | | 26 | 19
2023 | 10,115 | 1,264 | 327 | 84 | 100 | 143 | 937 | 8,807 | 3,162 | 5,213 | 432 | | 27 | 17
2022 | 10,122 | 1,208 | 309 | 58 | 110 | 141 | 899 | 8,852 | 3,075 | 5,239 | 538 | | 39 | 23
2021 | 9,531 | 1,207 | 338 | 79 | 111 | 148 | 869 | 8,275 | 2,863 | 4,995 | 417 | | 28 | 21
2020 | 9,626 | 1,158 | 296 | 72 | 98 | 126 | 862 | 8,425 | 2,890 | 5,018 | 517 | | 30 | 13
2019 | 9,770 | 1,088 | 283 | 82 | 80 | 121 | 805 | 8,644 | 2,885 | 5,247 | 512 | | 23 | 15
2018 | 9,476 | 1,116 | 340 | 72 | 119 | 149 | 776 | 8,313 | 2,674 | 5,106 | 533 | | 34 | 13
2017 | 9,426 | 992 | 252 | 51 | 79 | 122 | 740 | 8,376 | 2,697 | 5,050 | 629 | | 42 | 16
2016 | 9,342 | 1,075 | 291 | 67 | 103 | 121 | 784 | 8,216 | 2,559 | 5,073 | 584 | | 37 | 14
White:
2024 | 1,783,156 | 168,964 | 40,278 | 7,602 | 13,358 | 19,318 | 128,686 | 1,606,388 | 512,225 | 1,002,564 | 91,599 | | 6,021 | 1,783
2023 | 1,787,051 | 168,654 | 40,736 | 7,789 | 13,523 | 19,424 | 127,918 | 1,611,436 | 505,444 | 1,013,077 | 92,915 | | 6,050 | 911
2022 | 1,840,739 | 173,638 | 41,902 | 7,968 | 14,062 | 19,872 | 131,736 | 1,660,116 | 509,163 | 1,053,269 | 97,684 | | 5,974 | 1,011
2021 | 1,887,656 | 179,123 | 43,671 | 8,223 | 14,603 | 20,845 | 135,452 | 1,701,379 | 510,021 | 1,092,775 | 98,583 | | 5,939 | 1,215
2020 | 1,843,432 | 167,679 | 40,638 | 8,043 | 13,681 | 18,914 | 127,041 | 1,668,915 | 478,611 | 1,088,456 | 101,848 | | 5,837 | 1,001
2019 | 1,915,912 | 177,339 | 43,532 | 8,487 | 14,735 | 20,310 | 133,807 | 1,731,535 | 489,542 | 1,130,124 | 111,869 | | 6,114 | 924
2018 | 1,956,413 | 177,842 | 44,287 | 8,665 | 14,764 | 20,858 | 133,555 | 1,770,366 | 482,550 | 1,156,775 | 131,041 | | 7,281 | 924
2017 | 1,992,461 | 180,322 | 45,761 | 9,200 | 15,429 | 21,132 | 134,561 | 1,803,063 | 481,048 | 1,180,394 | 141,621 | | 8,025 | 1,051
2016 | 2,056,332 | 185,854 | 47,823 | 9,766 | 16,101 | 21,956 | 138,031 | 1,860,243 | 485,846 | 1,224,872 | 149,525 | | 8,826 | 1,409
Hispanic^4^ | Number
2024 | 984,092 | 98,970 | 25,175 | 6,016 | 8,602 | 10,557 | 73,795 | 882,739 | 303,261 | 539,534 | 39,944 | | 1,492 | 891
2023 | 945,200 | 95,755 | 24,735 | 5,966 | 8,354 | 10,415 | 71,020 | 847,391 | 287,252 | 520,655 | 39,484 | | 1,607 | 447
2022 | 937,421 | 94,306 | 24,408 | 5,653 | 8,289 | 10,466 | 69,898 | 841,129 | 282,083 | 517,597 | 41,449 | | 1,565 | 421
2021 | 885,916 | 90,613 | 23,620 | 5,534 | 8,021 | 10,065 | 66,993 | 793,509 | 264,132 | 492,466 | 36,911 | | 1,298 | 496
2020 | 866,713 | 85,224 | 21,790 | 5,241 | 7,273 | 9,276 | 63,434 | 779,828 | 251,210 | 490,413 | 38,205 | | 1,313 | 348
2019 | 886,467 | 88,354 | 23,116 | 5,620 | 7,699 | 9,797 | 65,238 | 796,333 | 253,964 | 500,856 | 41,513 | | 1,436 | 344
2018 | 886,210 | 86,186 | 22,637 | 5,490 | 7,467 | 9,680 | 63,549 | 797,905 | 248,463 | 503,429 | 46,013 | | 1,737 | 382
2017 | 898,764 | 86,393 | 23,025 | 5,605 | 7,635 | 9,785 | 63,368 | 809,882 | 247,788 | 513,342 | 48,752 | | 2,034 | 455
2016 | 918,447 | 86,691 | 23,195 | 5,649 | 7,665 | 9,881 | 63,496 | 828,783 | 247,999 | 530,951 | 49,833 | | 2,297 | 676

^1^Completed weeks based on the obstetric estimate of gestation; see User Guide in reference 8 in this report.

^2^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^3^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

^4^Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

The early preterm (less than 34 weeks) birth rate declined 1% from 2023 to 2024, from 2.76% to 2.72%, while the rate of late preterm births (34–36 weeks) increased 1%, from 7.64% to 7.69%. The 2024 early preterm rate is the lowest reported since 2020 (2.70%). The late preterm birth rate has risen 13% since the most recent low in 2014 (6.82%) (13).

Changes in the distribution of births delivered at term and later (37 weeks and higher) were also observed from 2023 to 2024. Following trends generally observed since 2014 (Figure 3) (23), the percentage of infants born early term (37–38 weeks) rose by 1% in 2024, from 29.84% to 30.26%, while full-term births (39–40 weeks) declined by 1% (54.94% to 54.61%). Late-term births (41 weeks) declined 2% (4.56% to 4.47%), and the percentage of post-term (42 weeks and higher) births declined from 0.26% to 0.25%. From 2007 to 2014, the early-term birth rate had generally declined, and the full- and late-term rates had increased (13). The percentage of post-term births generally declined from 2007 to 2019 but has fluctuated between 0.25% and 0.26% since (13) (Table 10).

Figure 3

Percent change in preterm, early, full, and late term births: United States, from 2014 to 2024

Figure 3 is a bar chart showing the percent change in preterm, early, full, and late term births from 2014 to 2024.

The preterm birth rate increased for Black mothers from 2023 to 2024 (14.65% to 14.86%) but did not change significantly for any of the other race and Hispanic-origin groups. Rates have risen for all groups from 2016 to 2024: American Indian and Alaska Native (from 11.39% to 12.64%), Asian (8.63% to 9.16%), Black (13.77% to 14.86%), Native Hawaiian and Other Pacific Islander (11.52% to 12.54%), White (9.04% to 9.49%), and Hispanic (9.45% to 10.07%) (Tables C and 10). For 2024, preterm birth rates ranged from a high of 14.86% for births to Black mothers to a low of 9.16% for Asian mothers (Table 10). Preterm rates for Hispanic subgroups ranged from 9.51% for Central and South American and 9.60% for Cuban to 11.58% for Puerto Rican women (Table D).

Analyzing births in singleton deliveries separately from all births can also be important because of the shorter average gestations of multiple births and their corresponding potential influence on preterm birth rates (see also “Multiple births” in this report). The 2024 preterm birth rate for singleton births only was 8.76%, a 1% increase from the 2023 rate of 8.71% (see Table E for 2024 data) (7). From 2007 to 2014, the singleton preterm rate declined from 8.59% to 7.74%, but it has risen 13% from 2014 to 2024 (13,24).

Table E Gestational age and birthweight characteristics, by plurality: United States, 2024

Plurality | Number of births | Early preterm^1^ | Preterm^2^ | Very low birthweight^3^ | Low birthweight^4^
| | Percent
All births | 3,628,934 | 2.72 | 10.41 | 1.33 | 8.52
Singleton | 3,517,151 | 2.15 | 8.76 | 1.06 | 7.00
Twin | 109,195 | 19.44 | 61.45 | 8.98 | 55.58
Triplet | 2,444 | 69.50 | 98.40 | 37.61 | 95.09
Quadruplet | 130 | 95.38 | 98.46 | 50.77 | 98.46
Quintuplet and higher-order multiples | 14 | 85.71 | 85.71 | 78.57 | 85.71

^1^Less than 34 completed weeks of gestation.

^2^Less than 37 completed weeks of gestation.

^3^Less than 1,500 grams (3 lb 4 oz).

^4^Less than 2,500 grams (5 lb 6 oz).

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

### Birthweight

The percentage of infants born low birthweight (LBW; less than 2,500 grams or 5 pounds, 8 ounces) in 2024 declined 1% from 2023, from 8.58% to 8.52%. While fluctuating somewhat over the last 4 decades, the rate has risen more than 20% since the 1980s and is up 7% since the most recent low in 2012 (7.99%) (Tables C and 11; see also Table 28 in the 2024 User Guide [8]) (13).

Table 11 Births, by birthweight: United States, 2010–2024, and age and race and Hispanic origin of mother: United States, 2016–2024

Race and Hispanic origin of mother and year | All births | Birthweight (grams)^1^
Race and Hispanic origin of mother and year | All births | Low birthweight | | | | | | | 2,500–2,999 | 3,000–3,499 | 3,500–3,999 | 4,000–4,499 | 4,500–4,999 | 5,000 or more | Not stated
Race and Hispanic origin of mother and year | All births | Total under 2,500 | Very low birthweight | | | | 1,500–1,999 | 2,000–2,499 | 2,500–2,999 | 3,000–3,499 | 3,500–3,999 | 4,000–4,499 | 4,500–4,999 | 5,000 or more | Not stated
Race and Hispanic origin of mother and year | All births | Total under 2,500 | Total under 1,500 | Less than 500 | 500–999 | 1,000–1,499 | 1,500–1,999 | 2,000–2,499 | 2,500–2,999 | 3,000–3,499 | 3,500–3,999 | 4,000–4,499 | 4,500–4,999 | 5,000 or more | Not stated
All races and origins^2^ | Number | Percent | | | | | | | | | | | | | Number
2024 | 3,628,934 | 8.52 | 1.33 | 0.13 | 0.48 | 0.71 | 1.64 | 5.56 | 19.76 | 39.12 | 25.52 | 6.19 | 0.81 | 0.09 | 2,993
2023 | 3,596,017 | 8.58 | 1.36 | 0.13 | 0.50 | 0.73 | 1.66 | 5.56 | 19.72 | 39.09 | 25.51 | 6.20 | 0.80 | 0.09 | 2,915
2022 | 3,667,758 | 8.60 | 1.36 | 0.13 | 0.49 | 0.73 | 1.67 | 5.57 | 19.68 | 39.00 | 25.58 | 6.23 | 0.82 | 0.09 | 2,990
2021 | 3,664,292 | 8.52 | 1.38 | 0.13 | 0.51 | 0.75 | 1.68 | 5.46 | 19.25 | 38.85 | 25.93 | 6.47 | 0.87 | 0.10 | 3,331
2020 | 3,613,647 | 8.24 | 1.34 | 0.13 | 0.49 | 0.71 | 1.61 | 5.29 | 19.15 | 38.94 | 26.18 | 6.51 | 0.87 | 0.10 | 2,977
2019 | 3,747,540 | 8.31 | 1.38 | 0.14 | 0.50 | 0.74 | 1.63 | 5.30 | 19.07 | 39.07 | 26.09 | 6.49 | 0.87 | 0.10 | 3,668
2018 | 3,791,712 | 8.28 | 1.38 | 0.14 | 0.50 | 0.74 | 1.62 | 5.28 | 18.75 | 38.76 | 26.44 | 6.72 | 0.94 | 0.11 | 2,932
2017 | 3,855,500 | 8.28 | 1.41 | 0.14 | 0.52 | 0.74 | 1.63 | 5.25 | 18.72 | 38.76 | 26.44 | 6.75 | 0.95 | 0.11 | 3,002
2016 | 3,945,875 | 8.17 | 1.40 | 0.14 | 0.52 | 0.74 | 1.59 | 5.17 | 18.54 | 38.76 | 26.60 | 6.85 | 0.97 | 0.11 | 4,518
2015 | 3,978,497 | 8.07 | 1.40 | 0.15 | 0.52 | 0.73 | 1.58 | 5.09 | 18.36 | 38.84 | 26.73 | 6.90 | 0.98 | 0.12 | 3,621
2014 | 3,988,076 | 8.00 | 1.40 | 0.15 | 0.52 | 0.74 | 1.56 | 5.04 | 18.27 | 38.80 | 26.88 | 6.94 | 0.99 | 0.12 | 3,270
2013 | 3,932,181 | 8.02 | 1.41 | 0.15 | 0.53 | 0.73 | 1.56 | 5.05 | 18.22 | 38.93 | 26.85 | 6.86 | 0.99 | 0.11 | 4,452
2012 | 3,952,841 | 7.99 | 1.42 | 0.15 | 0.54 | 0.73 | 1.56 | 5.01 | 18.28 | 39.00 | 26.81 | 6.83 | 0.97 | 0.12 | 4,008
2011 | 3,953,590 | 8.10 | 1.44 | 0.15 | 0.54 | 0.75 | 1.58 | 5.08 | 18.44 | 39.13 | 26.56 | 6.71 | 0.95 | 0.11 | 4,570
2010 | 3,999,386 | 8.15 | 1.45 | 0.15 | 0.55 | 0.75 | 1.59 | 5.11 | 18.63 | 39.21 | 26.41 | 6.58 | 0.92 | 0.11 | 3,964
Non-Hispanic, single race^3^
American Indian and Alaska Native:
2024 | 24,021 | 9.03 | 1.44 | 0.12 | 0.51 | 0.81 | 1.92 | 5.67 | 17.87 | 37.29 | 26.88 | 7.58 | 1.18 | 0.18 | 21
2023 | 24,571 | 8.65 | 1.38 | 0.12 | 0.51 | 0.76 | 1.72 | 5.56 | 18.20 | 36.48 | 27.02 | 8.18 | 1.21 | 0.25 | 23
2022 | 25,721 | 8.80 | 1.50 | 0.16 | 0.56 | 0.79 | 1.82 | 5.49 | 17.85 | 36.80 | 27.22 | 7.78 | 1.35 | 0.21 | 21
2021 | 26,124 | 8.11 | 1.26 | 0.11 | 0.48 | 0.67 | 1.74 | 5.11 | 17.75 | 36.71 | 27.34 | 8.55 | 1.26 | 0.28 | 19
2020 | 26,813 | 7.93 | 1.27 | 0.14 | 0.52 | 0.61 | 1.54 | 5.12 | 17.05 | 36.61 | 28.34 | 8.33 | 1.50 | 0.25 | 20
2019 | 28,450 | 8.04 | 1.29 | 0.12 | 0.44 | 0.74 | 1.58 | 5.17 | 16.94 | 36.76 | 28.34 | 8.16 | 1.55 | 0.21 | 18
2018 | 29,092 | 8.00 | 1.35 | 0.12 | 0.45 | 0.78 | 1.59 | 5.07 | 16.91 | 36.65 | 28.06 | 8.59 | 1.55 | 0.24 | 25
2017 | 29,957 | 8.25 | 1.41 | 0.15 | 0.49 | 0.77 | 1.72 | 5.12 | 16.91 | 35.90 | 28.45 | 8.68 | 1.59 | 0.23 | 26
2016 | 31,452 | 7.77 | 1.39 | 0.12 | 0.53 | 0.73 | 1.54 | 4.85 | 16.40 | 36.61 | 28.82 | 8.61 | 1.50 | 0.28 | 23
Asian:
2024 | 226,860 | 9.55 | 1.20 | 0.11 | 0.42 | 0.67 | 1.66 | 6.69 | 26.02 | 41.69 | 19.06 | 3.29 | 0.34 | 0.04 | 119
2023 | 215,738 | 9.44 | 1.14 | 0.09 | 0.41 | 0.64 | 1.70 | 6.59 | 25.85 | 41.73 | 19.24 | 3.37 | 0.33 | 0.05 | 108
2022 | 218,994 | 9.39 | 1.14 | 0.09 | 0.37 | 0.67 | 1.69 | 6.57 | 25.72 | 41.73 | 19.39 | 3.37 | 0.37 | 0.04 | 120
2021 | 213,813 | 9.24 | 1.17 | 0.10 | 0.41 | 0.67 | 1.67 | 6.40 | 25.35 | 41.84 | 19.65 | 3.49 | 0.39 | 0.04 | 136
2020 | 219,068 | 8.54 | 1.03 | 0.08 | 0.36 | 0.59 | 1.54 | 5.96 | 25.17 | 42.36 | 19.98 | 3.53 | 0.37 | 0.05 | 91
2019 | 238,769 | 8.67 | 1.09 | 0.10 | 0.38 | 0.61 | 1.54 | 6.05 | 24.59 | 42.38 | 20.31 | 3.61 | 0.40 | 0.05 | 176
2018 | 240,798 | 8.58 | 1.11 | 0.10 | 0.37 | 0.63 | 1.54 | 5.94 | 24.44 | 42.23 | 20.61 | 3.68 | 0.41 | 0.05 | 101
2017 | 249,250 | 8.52 | 1.13 | 0.10 | 0.40 | 0.64 | 1.57 | 5.82 | 24.26 | 42.45 | 20.59 | 3.72 | 0.41 | 0.05 | 119
2016 | 254,471 | 8.43 | 1.09 | 0.09 | 0.37 | 0.63 | 1.50 | 5.84 | 24.12 | 42.42 | 20.74 | 3.79 | 0.43 | 0.05 | 236
Black:
2024 | 473,377 | 15.01 | 2.83 | 0.34 | 1.12 | 1.37 | 2.93 | 9.25 | 26.49 | 37.10 | 17.46 | 3.40 | 0.47 | 0.07 | 505
2023 | 491,494 | 14.80 | 2.86 | 0.34 | 1.12 | 1.40 | 2.87 | 9.07 | 26.48 | 37.27 | 17.51 | 3.45 | 0.44 | 0.06 | 491
2022 | 511,439 | 14.75 | 2.89 | 0.34 | 1.15 | 1.40 | 2.85 | 9.01 | 26.40 | 37.23 | 17.57 | 3.52 | 0.47 | 0.06 | 528
2021 | 517,889 | 14.66 | 2.91 | 0.32 | 1.15 | 1.44 | 2.91 | 8.84 | 26.08 | 37.38 | 17.74 | 3.58 | 0.49 | 0.06 | 580
2020 | 529,811 | 14.19 | 2.86 | 0.34 | 1.13 | 1.39 | 2.79 | 8.53 | 25.90 | 37.60 | 18.14 | 3.61 | 0.49 | 0.07 | 569
2019 | 548,075 | 14.15 | 2.94 | 0.36 | 1.15 | 1.43 | 2.79 | 8.43 | 25.75 | 37.96 | 18.01 | 3.59 | 0.47 | 0.06 | 688
2018 | 552,029 | 14.07 | 2.92 | 0.35 | 1.16 | 1.41 | 2.79 | 8.35 | 25.44 | 37.90 | 18.33 | 3.68 | 0.51 | 0.07 | 571
2017 | 560,715 | 13.89 | 2.95 | 0.36 | 1.18 | 1.41 | 2.72 | 8.22 | 25.44 | 37.96 | 18.37 | 3.76 | 0.51 | 0.07 | 642
2016 | 558,622 | 13.68 | 2.95 | 0.37 | 1.20 | 1.38 | 2.67 | 8.06 | 25.38 | 38.24 | 18.42 | 3.69 | 0.52 | 0.07 | 936
Native Hawaiian and Other Pacific Islander:
2024 | 10,375 | 9.49 | 1.62 | 0.11 | 0.61 | 0.91 | 1.96 | 5.91 | 19.71 | 37.99 | 24.58 | 6.85 | 1.16 | 0.22 | 2
2023 | 10,115 | 9.34 | 1.55 | 0.17 | 0.59 | 0.79 | 1.69 | 6.09 | 19.95 | 37.73 | 24.32 | 6.99 | 1.39 | 0.27 | 6
2022 | 10,122 | 8.51 | 1.46 | 0.17 | 0.43 | 0.86 | 1.59 | 5.46 | 19.95 | 37.64 | 25.43 | 7.08 | 1.08 | 0.32 | 7
2021 | 9,531 | 9.29 | 1.69 | 0.13 | 0.71 | 0.85 | 1.76 | 5.84 | 19.15 | 36.96 | 25.01 | 7.61 | 1.70 | 0.26 | 8
2020 | 9,626 | 8.44 | 1.49 | 0.15 | 0.44 | 0.90 | 1.63 | 5.32 | 18.45 | 38.40 | 25.81 | 7.14 | 1.38 | 0.37 | 8
2019 | 9,770 | 7.56 | 1.33 | 0.17 | 0.51 | 0.65 | 1.46 | 4.78 | 20.08 | 37.70 | 25.34 | 7.62 | 1.51 | 0.18 | 11
2018 | 9,476 | 8.97 | 1.48 | 0.13 | 0.58 | 0.77 | 1.73 | 5.76 | 19.15 | 36.83 | 25.55 | 7.71 | 1.56 | 0.22 | 9
2017 | 9,426 | 7.74 | 1.15 | 0.13 | 0.41 | 0.61 | 1.72 | 4.87 | 18.77 | 36.90 | 26.61 | 8.06 | 1.66 | 0.27 | 6
2016 | 9,342 | 7.67 | 1.47 | 0.11 | 0.59 | 0.77 | 1.60 | 4.61 | 18.51 | 37.15 | 26.37 | 8.31 | 1.57 | 0.41 | 7
White:
2024 | 1,783,156 | 6.97 | 0.99 | 0.09 | 0.33 | 0.56 | 1.37 | 4.61 | 16.85 | 38.35 | 29.03 | 7.70 | 1.01 | 0.10 | 1,115
2023 | 1,787,051 | 7.04 | 1.00 | 0.08 | 0.34 | 0.58 | 1.38 | 4.66 | 16.85 | 38.43 | 28.91 | 7.67 | 1.01 | 0.10 | 1,069
2022 | 1,840,739 | 7.12 | 1.01 | 0.08 | 0.34 | 0.59 | 1.41 | 4.70 | 16.84 | 38.38 | 28.91 | 7.65 | 0.99 | 0.10 | 1,125
2021 | 1,887,656 | 7.03 | 1.02 | 0.08 | 0.35 | 0.59 | 1.41 | 4.60 | 16.52 | 38.18 | 29.21 | 7.89 | 1.07 | 0.11 | 1,313
2020 | 1,843,432 | 6.84 | 0.99 | 0.08 | 0.34 | 0.56 | 1.35 | 4.50 | 16.37 | 38.18 | 29.46 | 7.96 | 1.07 | 0.12 | 1,144
2019 | 1,915,912 | 6.89 | 1.02 | 0.08 | 0.35 | 0.59 | 1.39 | 4.49 | 16.35 | 38.24 | 29.37 | 7.96 | 1.08 | 0.11 | 1,550
2018 | 1,956,413 | 6.91 | 1.02 | 0.09 | 0.34 | 0.58 | 1.38 | 4.52 | 16.01 | 37.80 | 29.74 | 8.25 | 1.16 | 0.12 | 1,259
2017 | 1,992,461 | 7.00 | 1.05 | 0.09 | 0.36 | 0.60 | 1.40 | 4.54 | 16.05 | 37.68 | 29.70 | 8.28 | 1.17 | 0.12 | 1,211
2016 | 2,056,332 | 6.97 | 1.07 | 0.09 | 0.37 | 0.61 | 1.39 | 4.51 | 15.88 | 37.59 | 29.82 | 8.39 | 1.21 | 0.12 | 2,212
Hispanic^4^ | Number | Percent | | | | | | | | | | | | | Number
2024 | 984,092 | 7.85 | 1.23 | 0.12 | 0.45 | 0.65 | 1.47 | 5.15 | 20.35 | 40.98 | 24.62 | 5.44 | 0.68 | 0.09 | 546
2023 | 945,200 | 7.92 | 1.26 | 0.13 | 0.47 | 0.66 | 1.52 | 5.14 | 20.19 | 40.84 | 24.79 | 5.47 | 0.70 | 0.09 | 493
2022 | 937,421 | 7.87 | 1.24 | 0.12 | 0.45 | 0.67 | 1.51 | 5.12 | 20.15 | 40.66 | 24.93 | 5.54 | 0.75 | 0.10 | 479
2021 | 885,916 | 7.82 | 1.28 | 0.12 | 0.47 | 0.69 | 1.52 | 5.02 | 19.55 | 40.58 | 25.35 | 5.82 | 0.78 | 0.10 | 594
2020 | 866,713 | 7.40 | 1.19 | 0.12 | 0.45 | 0.63 | 1.43 | 4.77 | 19.41 | 40.63 | 25.74 | 5.92 | 0.79 | 0.11 | 436
2019 | 886,467 | 7.55 | 1.27 | 0.12 | 0.47 | 0.68 | 1.45 | 4.83 | 19.23 | 40.83 | 25.62 | 5.89 | 0.78 | 0.10 | 575
2018 | 886,210 | 7.49 | 1.24 | 0.12 | 0.46 | 0.66 | 1.43 | 4.81 | 19.01 | 40.64 | 25.90 | 6.02 | 0.83 | 0.11 | 381
2017 | 898,764 | 7.43 | 1.26 | 0.13 | 0.47 | 0.66 | 1.42 | 4.76 | 18.86 | 40.76 | 25.95 | 6.02 | 0.85 | 0.11 | 428
2016 | 918,447 | 7.32 | 1.24 | 0.13 | 0.46 | 0.65 | 1.41 | 4.68 | 18.76 | 40.79 | 26.06 | 6.10 | 0.85 | 0.12 | 556
All races and origins^2^ | Number
2024 | 3,628,934 | 308,966 | 48,133 | 4,880 | 17,485 | 25,768 | 59,409 | 201,424 | 716,476 | 1,418,311 | 925,370 | 224,308 | 29,198 | 3,312 | 2,993
2023 | 3,596,017 | 308,263 | 48,832 | 4,780 | 17,826 | 26,226 | 59,591 | 199,840 | 708,655 | 1,404,466 | 916,755 | 222,852 | 28,842 | 3,269 | 2,915
2022 | 3,667,758 | 315,288 | 49,871 | 4,879 | 18,087 | 26,905 | 61,182 | 204,235 | 721,299 | 1,429,131 | 937,571 | 228,179 | 29,923 | 3,377 | 2,990
2021 | 3,664,292 | 311,932 | 50,551 | 4,629 | 18,512 | 27,410 | 61,585 | 199,796 | 704,766 | 1,422,368 | 949,323 | 236,987 | 31,964 | 3,621 | 3,331
2020 | 3,613,647 | 297,604 | 48,326 | 4,790 | 17,805 | 25,731 | 58,162 | 191,116 | 691,557 | 1,405,907 | 945,295 | 235,023 | 31,500 | 3,784 | 2,977
2019 | 3,747,540 | 311,245 | 51,733 | 5,189 | 18,839 | 27,705 | 61,205 | 198,307 | 713,859 | 1,462,658 | 976,609 | 243,153 | 32,694 | 3,654 | 3,668
2018 | 3,791,712 | 313,752 | 52,171 | 5,303 | 18,970 | 27,898 | 61,509 | 200,072 | 710,444 | 1,468,639 | 1,001,803 | 254,704 | 35,435 | 4,003 | 2,932
2017 | 3,855,500 | 318,873 | 54,135 | 5,470 | 19,979 | 28,686 | 62,605 | 202,133 | 721,165 | 1,493,081 | 1,018,613 | 260,042 | 36,493 | 4,231 | 3,002
2016 | 3,945,875 | 321,839 | 55,110 | 5,710 | 20,323 | 29,077 | 62,863 | 203,866 | 730,710 | 1,527,707 | 1,048,476 | 269,865 | 38,264 | 4,496 | 4,518
2015 | 3,978,497 | 320,869 | 55,592 | 5,863 | 20,689 | 29,040 | 62,862 | 202,415 | 729,673 | 1,544,024 | 1,062,456 | 274,404 | 38,796 | 4,654 | 3,621
2014 | 3,988,076 | 318,847 | 55,947 | 5,936 | 20,721 | 29,290 | 61,992 | 200,908 | 727,987 | 1,546,274 | 1,071,007 | 276,592 | 39,353 | 4,746 | 3,270
2013 | 3,932,181 | 315,099 | 55,458 | 5,945 | 20,866 | 28,647 | 61,238 | 198,403 | 715,764 | 1,529,258 | 1,054,767 | 269,594 | 38,834 | 4,413 | 4,452
2012 | 3,952,841 | 315,709 | 56,252 | 5,947 | 21,432 | 28,873 | 61,499 | 197,958 | 721,840 | 1,540,161 | 1,058,604 | 269,581 | 38,288 | 4,650 | 4,008
2011 | 3,953,590 | 319,711 | 56,754 | 5,942 | 21,289 | 29,523 | 62,504 | 200,453 | 728,201 | 1,545,355 | 1,048,902 | 265,040 | 37,475 | 4,336 | 4,570
2010 | 3,999,386 | 325,563 | 57,841 | 5,980 | 22,015 | 29,846 | 63,427 | 204,295 | 744,181 | 1,566,755 | 1,055,004 | 262,997 | 36,706 | 4,216 | 3,964
Non-Hispanic, single race^3^
American Indian and Alaska Native:
2024 | 24,021 | 2,167 | 346 | 29 | 123 | 194 | 461 | 1,360 | 4,288 | 8,950 | 6,450 | 1,818 | 283 | 44 | 21
2023 | 24,571 | 2,124 | 339 | 29 | 124 | 186 | 421 | 1,364 | 4,468 | 8,956 | 6,633 | 2,009 | 297 | 61 | 23
2022 | 25,721 | 2,262 | 385 | 40 | 143 | 202 | 467 | 1,410 | 4,587 | 9,457 | 6,995 | 1,999 | 346 | 54 | 21
2021 | 26,124 | 2,117 | 329 | 29 | 126 | 174 | 453 | 1,335 | 4,634 | 9,583 | 7,138 | 2,232 | 328 | 73 | 19
2020 | 26,813 | 2,125 | 340 | 38 | 138 | 164 | 413 | 1,372 | 4,567 | 9,809 | 7,592 | 2,233 | 401 | 66 | 20
2019 | 28,450 | 2,286 | 366 | 33 | 124 | 209 | 449 | 1,471 | 4,816 | 10,451 | 8,057 | 2,321 | 442 | 59 | 18
2018 | 29,092 | 2,326 | 392 | 34 | 132 | 226 | 461 | 1,473 | 4,915 | 10,652 | 8,155 | 2,497 | 451 | 71 | 25
2017 | 29,957 | 2,469 | 421 | 44 | 148 | 229 | 515 | 1,533 | 5,060 | 10,744 | 8,515 | 2,599 | 476 | 68 | 26
2016 | 31,452 | 2,442 | 436 | 39 | 166 | 231 | 483 | 1,523 | 5,155 | 11,507 | 9,058 | 2,706 | 473 | 88 | 23
Asian:
2024 | 226,860 | 21,656 | 2,722 | 243 | 954 | 1,525 | 3,756 | 15,178 | 59,009 | 94,518 | 43,224 | 7,468 | 770 | 96 | 119
2023 | 215,738 | 20,355 | 2,466 | 184 | 894 | 1,388 | 3,673 | 14,216 | 55,732 | 89,988 | 41,482 | 7,256 | 713 | 104 | 108
2022 | 218,994 | 20,559 | 2,493 | 205 | 815 | 1,473 | 3,693 | 14,373 | 56,284 | 91,332 | 42,429 | 7,383 | 806 | 81 | 120
2021 | 213,813 | 19,739 | 2,510 | 217 | 868 | 1,425 | 3,562 | 13,667 | 54,162 | 89,392 | 41,994 | 7,457 | 839 | 94 | 136
2020 | 219,068 | 18,698 | 2,258 | 179 | 794 | 1,285 | 3,381 | 13,059 | 55,114 | 92,758 | 43,741 | 7,739 | 820 | 107 | 91
2019 | 238,769 | 20,692 | 2,589 | 235 | 900 | 1,454 | 3,678 | 14,425 | 58,670 | 101,110 | 48,459 | 8,604 | 950 | 108 | 176
2018 | 240,798 | 20,654 | 2,662 | 242 | 898 | 1,522 | 3,697 | 14,295 | 58,817 | 101,651 | 49,617 | 8,849 | 978 | 131 | 101
2017 | 249,250 | 21,222 | 2,815 | 244 | 988 | 1,583 | 3,920 | 14,487 | 60,439 | 105,768 | 51,296 | 9,275 | 1,014 | 117 | 119
2016 | 254,471 | 21,437 | 2,777 | 240 | 928 | 1,609 | 3,821 | 14,839 | 61,329 | 107,857 | 52,739 | 9,645 | 1,093 | 135 | 236
Black:
2024 | 473,377 | 70,984 | 13,368 | 1,610 | 5,283 | 6,475 | 13,865 | 43,751 | 125,265 | 175,443 | 82,569 | 16,084 | 2,201 | 326 | 505
2023 | 491,494 | 72,673 | 14,048 | 1,654 | 5,500 | 6,894 | 14,072 | 44,553 | 130,032 | 182,975 | 85,981 | 16,919 | 2,138 | 285 | 491
2022 | 511,439 | 75,359 | 14,774 | 1,723 | 5,892 | 7,159 | 14,557 | 46,028 | 134,893 | 190,192 | 89,775 | 17,984 | 2,387 | 321 | 528
2021 | 517,889 | 75,837 | 15,036 | 1,639 | 5,958 | 7,439 | 15,068 | 45,733 | 134,892 | 193,393 | 91,772 | 18,543 | 2,540 | 332 | 580
2020 | 529,811 | 75,085 | 15,146 | 1,806 | 5,985 | 7,355 | 14,785 | 45,154 | 137,053 | 198,979 | 96,025 | 19,101 | 2,618 | 381 | 569
2019 | 548,075 | 77,475 | 16,089 | 1,954 | 6,315 | 7,820 | 15,261 | 46,125 | 140,963 | 207,795 | 98,585 | 19,641 | 2,593 | 335 | 688
2018 | 552,029 | 77,584 | 16,127 | 1,941 | 6,406 | 7,780 | 15,411 | 46,046 | 140,295 | 209,028 | 101,089 | 20,285 | 2,806 | 371 | 571
2017 | 560,715 | 77,815 | 16,544 | 2,024 | 6,597 | 7,923 | 15,228 | 46,043 | 142,459 | 212,599 | 102,878 | 21,065 | 2,854 | 403 | 642
2016 | 558,622 | 76,299 | 16,465 | 2,083 | 6,675 | 7,707 | 14,885 | 44,949 | 141,557 | 213,260 | 102,702 | 20,571 | 2,880 | 417 | 936
Native Hawaiian and Other Pacific Islander:
2024 | 10,375 | 984 | 168 | 11 | 63 | 94 | 203 | 613 | 2,044 | 3,941 | 2,550 | 711 | 120 | 23 | 2
2023 | 10,115 | 944 | 157 | 17 | 60 | 80 | 171 | 616 | 2,017 | 3,814 | 2,459 | 707 | 141 | 27 | 6
2022 | 10,122 | 861 | 148 | 17 | 44 | 87 | 161 | 552 | 2,018 | 3,807 | 2,572 | 716 | 109 | 32 | 7
2021 | 9,531 | 885 | 161 | 12 | 68 | 81 | 168 | 556 | 1,824 | 3,520 | 2,382 | 725 | 162 | 25 | 8
2020 | 9,626 | 812 | 143 | 14 | 42 | 87 | 157 | 512 | 1,775 | 3,693 | 2,482 | 687 | 133 | 36 | 8
2019 | 9,770 | 738 | 130 | 17 | 50 | 63 | 142 | 466 | 1,960 | 3,679 | 2,473 | 744 | 147 | 18 | 11
2018 | 9,476 | 849 | 140 | 12 | 55 | 73 | 164 | 545 | 1,813 | 3,487 | 2,419 | 730 | 148 | 21 | 9
2017 | 9,426 | 729 | 108 | 12 | 39 | 57 | 162 | 459 | 1,768 | 3,476 | 2,507 | 759 | 156 | 25 | 6
2016 | 9,342 | 716 | 137 | 10 | 55 | 72 | 149 | 430 | 1,728 | 3,468 | 2,462 | 776 | 147 | 38 | 7
White:
2024 | 1,783,156 | 124,145 | 17,559 | 1,553 | 5,941 | 10,065 | 24,346 | 82,240 | 300,233 | 683,397 | 517,241 | 137,153 | 18,061 | 1,811 | 1,115
2023 | 1,787,051 | 125,668 | 17,914 | 1,436 | 6,072 | 10,406 | 24,610 | 83,144 | 300,962 | 686,320 | 516,300 | 136,914 | 17,980 | 1,838 | 1,069
2022 | 1,840,739 | 130,976 | 18,565 | 1,521 | 6,266 | 10,778 | 25,879 | 86,532 | 309,819 | 706,130 | 531,886 | 140,719 | 18,242 | 1,842 | 1,125
2021 | 1,887,656 | 132,551 | 19,157 | 1,471 | 6,589 | 11,097 | 26,587 | 86,807 | 311,569 | 720,236 | 550,917 | 148,810 | 20,181 | 2,079 | 1,313
2020 | 1,843,432 | 126,034 | 18,182 | 1,521 | 6,263 | 10,398 | 24,881 | 82,971 | 301,674 | 703,331 | 542,775 | 146,626 | 19,719 | 2,129 | 1,144
2019 | 1,915,912 | 131,959 | 19,443 | 1,587 | 6,643 | 11,213 | 26,572 | 85,944 | 312,909 | 732,022 | 562,273 | 152,340 | 20,720 | 2,139 | 1,550
2018 | 1,956,413 | 135,185 | 19,872 | 1,721 | 6,719 | 11,432 | 26,964 | 88,349 | 313,105 | 739,031 | 581,499 | 161,395 | 22,645 | 2,294 | 1,259
2017 | 1,992,461 | 139,358 | 20,981 | 1,752 | 7,233 | 11,996 | 27,968 | 90,409 | 319,523 | 750,331 | 591,376 | 164,898 | 23,299 | 2,465 | 1,211
2016 | 2,056,332 | 143,254 | 21,979 | 1,888 | 7,565 | 12,526 | 28,578 | 92,697 | 326,279 | 772,165 | 612,641 | 172,434 | 24,781 | 2,566 | 2,212
Hispanic^4^
2024 | 984,092 | 77,175 | 12,055 | 1,195 | 4,464 | 6,396 | 14,488 | 50,632 | 200,159 | 403,008 | 242,125 | 53,477 | 6,716 | 886 | 546
2023 | 945,200 | 74,860 | 11,932 | 1,216 | 4,486 | 6,230 | 14,335 | 48,593 | 190,745 | 385,797 | 234,159 | 51,672 | 6,633 | 841 | 493
2022 | 937,421 | 73,767 | 11,622 | 1,121 | 4,262 | 6,239 | 14,180 | 47,965 | 188,801 | 380,957 | 233,558 | 51,942 | 7,016 | 901 | 479
2021 | 885,916 | 69,238 | 11,336 | 1,024 | 4,179 | 6,133 | 13,471 | 44,431 | 173,097 | 359,282 | 224,461 | 51,483 | 6,866 | 895 | 594
2020 | 866,713 | 64,092 | 10,344 | 998 | 3,890 | 5,456 | 12,394 | 41,354 | 168,111 | 351,994 | 223,005 | 51,290 | 6,857 | 928 | 436
2019 | 886,467 | 66,912 | 11,223 | 1,105 | 4,135 | 5,983 | 12,869 | 42,820 | 170,366 | 361,725 | 226,969 | 52,185 | 6,880 | 855 | 575
2018 | 886,210 | 66,310 | 11,006 | 1,084 | 4,040 | 5,882 | 12,706 | 42,598 | 168,418 | 359,966 | 229,450 | 53,359 | 7,358 | 968 | 381
2017 | 898,764 | 66,766 | 11,275 | 1,137 | 4,229 | 5,909 | 12,772 | 42,719 | 169,467 | 366,198 | 233,157 | 54,096 | 7,631 | 1,021 | 428
2016 | 918,447 | 67,210 | 11,378 | 1,175 | 4,237 | 5,966 | 12,910 | 42,922 | 172,171 | 374,434 | 239,210 | 55,983 | 7,770 | 1,113 | 556

^1^Equivalents of gram weights in pounds and ounces are shown in the User Guide; see reference 8 in this report.

^2^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^3^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

^4^Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

The 2024 very low birthweight (less than 1,500 grams) rate declined 2%, from 1.36% to 1.33%. The very low birthweight rate is down from the high of 1.49% for 2005–2007 (13). The percentage of moderately low birthweight infants (1,500–2,499 grams) was 7.19% in 2024, not significantly lower than in 2023 (7.22%). Moderately low birthweight levels for 2016–2024 have matched or surpassed the peak reported for 2006 (6.77%) (Tables C and 11; see also Table 28 in the 2024 User Guide [8]).

From 2023 to 2024, the LBW rate increased for births to Black women (14.80% to 15.01%), declined for births to White women (7.04% to 6.97%), and did not change significantly for all other race and Hispanic-origin groups. Since 2016, LBW rates have risen for all groups except White women (6.97% in 2016): American Indian and Alaska Native (7.77% to 9.03%), Asian (8.43% to 9.55%), Black (13.68% to 15.01%), Native Hawaiian and Other Pacific Islander (7.67% to 9.49%), and Hispanic (7.32% to 7.85% (Tables C and 11). See Tables C and D, and Tables 29 and 30 in the 2024 User Guide (8), for 2024 very low birthweight and LBW rates by state and race and Hispanic origin.

The LBW rate among singleton births only was unchanged from 2023 at 7.00% in 2024 (7); see Table E for 2024 data. Examining births in singleton deliveries separately can be informative because multiple births tend to be born smaller than singleton births, and changes in multiple-birth incidence can influence overall LBW levels.

### Multiple births

The 2024 twin birth rate was 30.1 twins per 1,000 births, a 2% decline from the 2023 rate of 30.7 (Table 12; see also Table 33 in the 2024 User Guide [8]) and the lowest rate reported in more than 20 years (2002) (13). The twinning rate (births in twin deliveries per 1,000 total births) rose 76% from 1980 to 2009 (from 18.9 to 33.2), was generally stable from 2009 to 2012, and then rose for 2013 and 2014 before declining 11% from 2014 to 2024 (13).

Table 12 Twin, triplet, and higher-order multiple births: United States, 2010–2024, and by race and Hispanic origin of mother: United States, 2016–2024

Race and Hispanic origin and year | Total | Twin | Triplet and higher order^1^ | Multiple birth rate | Twin birth rate | Triplet and higher-order birth rate^1^
All races and origins^2^ | Number | | | Rate per 1,000 | | Rate per 100,000
2024 | 3,628,934 | 109,195 | 2,588 | 30.8 | 30.1 | 71.3
2023 | 3,596,017 | 110,393 | 2,653 | 31.4 | 30.7 | 73.8
2022 | 3,667,758 | 114,483 | 2,895 | 32.0 | 31.2 | 78.9
2021 | 3,664,292 | 114,161 | 2,933 | 32.0 | 31.2 | 80.0
2020 | 3,613,647 | 112,437 | 2,875 | 31.9 | 31.1 | 79.6
2019 | 3,747,540 | 120,291 | 3,286 | 33.0 | 32.1 | 87.7
2018 | 3,791,712 | 123,536 | 3,525 | 33.5 | 32.6 | 93.0
2017 | 3,855,500 | 128,310 | 3,917 | 34.3 | 33.3 | 101.6
2016 | 3,945,875 | 131,723 | 4,003 | 34.4 | 33.4 | 101.4
2015 | 3,978,497 | 133,155 | 4,123 | 34.5 | 33.5 | 103.6
2014 | 3,988,076 | 135,336 | 4,526 | 35.1 | 33.9 | 113.5
2013 | 3,932,181 | 132,324 | 4,700 | 34.8 | 33.7 | 119.5
2012 | 3,952,841 | 131,024 | 4,919 | 34.4 | 33.1 | 124.4
2011 | 3,953,590 | 131,269 | 5,417 | 34.6 | 33.2 | 137.0
2010 | 3,999,386 | 132,562 | 5,503 | 34.5 | 33.1 | 137.6
Non-Hispanic, single race^3^
American Indian and Alaska Native:
2024 | 24,021 | 628 | 20 | 27.0 | 26.1 | 83.3
2023 | 24,571 | 668 | * | 27.3 | 27.2 | *
2022 | 25,721 | 682 | 15 | 27.1 | 26.5 | 58.3
2021 | 26,124 | 713 | * | 27.4 | 27.3 | *
2020 | 26,813 | 620 | * | 23.4 | 23.1 | *
2019 | 28,450 | 698 | 13 | 25.0 | 24.5 | 45.7
2018 | 29,092 | 760 | * | 26.3 | 26.1 | *
2017 | 29,957 | 802 | 11 | 27.1 | 26.8 | 36.7
2016 | 31,452 | 888 | * | 28.4 | 28.2 | *
Asian:
2024 | 226,860 | 5,294 | 117 | 23.9 | 23.3 | 51.6
2023 | 215,738 | 5,300 | 110 | 25.1 | 24.6 | 51.0
2022 | 218,994 | 5,177 | 110 | 24.1 | 23.6 | 50.2
2021 | 213,813 | 4,985 | 90 | 23.7 | 23.3 | 42.1
2020 | 219,068 | 5,159 | 100 | 24.0 | 23.5 | 45.6
2019 | 238,769 | 6,567 | 123 | 28.0 | 27.5 | 51.5
2018 | 240,798 | 6,784 | 142 | 28.8 | 28.2 | 59.0
2017 | 249,250 | 7,216 | 150 | 29.6 | 29.0 | 60.2
2016 | 254,471 | 7,779 | 189 | 31.3 | 30.6 | 74.3
Black:
2024 | 473,377 | 19,874 | 522 | 43.1 | 42.0 | 110.3
2023 | 491,494 | 20,347 | 535 | 42.5 | 41.4 | 108.9
2022 | 511,439 | 21,163 | 556 | 42.5 | 41.4 | 108.7
2021 | 517,889 | 21,047 | 424 | 41.5 | 40.6 | 81.9
2020 | 529,811 | 21,554 | 521 | 41.7 | 40.7 | 98.3
2019 | 548,075 | 22,397 | 589 | 41.9 | 40.9 | 107.5
2018 | 552,029 | 22,502 | 658 | 42.0 | 40.8 | 119.2
2017 | 560,715 | 22,982 | 671 | 42.2 | 41.0 | 119.7
2016 | 558,622 | 22,267 | 628 | 41.0 | 39.9 | 112.4
Native Hawaiian and Other Pacific Islander:
2024 | 10,375 | 254 | * | 24.8 | 24.5 | *
2023 | 10,115 | 270 | * | 27.0 | 26.7 | *
2022 | 10,122 | 232 | * | 22.9 | 22.9 | *
2021 | 9,531 | 238 | * | 25.0 | 25.0 | *
2020 | 9,626 | 253 | * | 26.9 | 26.3 | *
2019 | 9,770 | 239 | * | 24.5 | 24.5 | *
2018 | 9,476 | 250 | 15 | 28.0 | 26.4 | 158.3
2017 | 9,426 | 237 | * | 25.5 | 25.1 | *
2016 | 9,342 | 228 | * | 24.7 | 24.4 | *
White:
2024 | 1,783,156 | 55,792 | 1,349 | 32.0 | 31.3 | 75.7
2023 | 1,787,051 | 56,648 | 1,360 | 32.5 | 31.7 | 76.1
2022 | 1,840,739 | 59,969 | 1,549 | 33.4 | 32.6 | 84.2
2021 | 1,887,656 | 61,438 | 1,762 | 33.5 | 32.5 | 93.3
2020 | 1,843,432 | 60,082 | 1,664 | 33.5 | 32.6 | 90.3
2019 | 1,915,912 | 64,011 | 1,865 | 34.4 | 33.4 | 97.3
2018 | 1,956,413 | 67,203 | 1,996 | 35.4 | 34.4 | 102.0
2017 | 1,992,461 | 70,704 | 2,324 | 36.7 | 35.5 | 116.6
2016 | 2,056,332 | 73,425 | 2,502 | 36.9 | 35.7 | 121.7
Hispanic^4^
2024 | 984,092 | 23,076 | 485 | 23.9 | 23.4 | 49.3
2023 | 945,200 | 22,954 | 535 | 24.9 | 24.3 | 56.6
2022 | 937,421 | 22,992 | 575 | 25.1 | 24.5 | 61.3
2021 | 885,916 | 21,401 | 554 | 24.8 | 24.2 | 62.5
2020 | 866,713 | 20,709 | 488 | 24.5 | 23.9 | 56.3
2019 | 886,467 | 21,811 | 590 | 25.3 | 24.6 | 66.6
2018 | 886,210 | 21,654 | 573 | 25.1 | 24.4 | 64.7
2017 | 898,764 | 22,041 | 614 | 25.2 | 24.5 | 68.3
2016 | 918,447 | 22,625 | 538 | 25.2 | 24.6 | 58.6

^*^ Estimate does not meet National Center for Health Statistics standards of reliability.

^1^Triplet, quadruplet, quintuplet, and higher-order multiple deliveries.

^2^Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

^3^Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

^4^Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

The triplet and higher-order multiple birth rate (triplet/+) was 71.3 per 100,000 births for 2024, a nonsignificant decline from 2023 (73.8) (Table 12). The 2024 rate of triplet/+ births is down 63% from the 1998 peak (193.5) (13). The triplet/+ birth rate (number of triplets, quadruplets, quintuplets, and other higher-order multiples per 100,000 births) rose more than 400% from 1980 to 1998 (13).

A total of 109,195 infants were born in twin deliveries in 2024, down 1% from the 110,393 twins reported in 2023 (Table 12); the number of twin births has declined 19% since the high for 2014 (135,336). The number of infants born in triplet/+ deliveries declined 2% in 2024 to 2,588 births from 2,653 in 2023 (change not significant). The number of triplet/+ births is down 66% since the 2003 high when 7,663 triplet/+ births were reported (13). The 2024 number included 2,444 triplets, 130 quadruplets, and 14 quintuplet and higher-order multiple births. See Table E for the number of births and percentages of preterm and LBW births by plurality.

Twin birth rates declined from 2023 to 2024 for Asian (24.6 per 1,000 to 23.3), White (31.7 to 31.3), and Hispanic (24.3 to 23.4) women; changes for American Indian and Alaska Native (27.2 to 26.1), Native Hawaiian and Other Pacific Islander (26.7 to 24.5), and Black (41.4 to 42.0) women were not significant (Tables C and 12). From 2016 to 2024, twinning rates declined for Asian, White, and Hispanic women, increased for Black women, and did not change significantly for American Indian and Alaska Native and Native Hawaiian and Other Pacific Islander women.

From 2023 to 2024, triplet/+ birth rates declined among Hispanic women (56.6 per 100,000 to 49.3) and were essentially unchanged for Asian (51.0 to 51.6), Black (108.9 to 110.3), and White (76.1 to 75.7) women. (Numbers of triplet/+ births were too small to calculate rates for American Indian and Alaska Native and Native Hawaiian and Other Pacific Islander women.) From 2016 to 2024, triplet/+ rates declined for Asian, White, and Hispanic women and were not significantly changed for Black women (Table 12; see also Table D for 2024 twin and triplet/+ rates for Hispanic subgroups). For state-specific twin and triplet/+ rates, see Table 34 in the 2024 User Guide (8).

## Acknowledgments

This report was prepared in the Division of Vital Statistics under the general direction of Director Paul Sutton; Robert Anderson, Chief, Statistical Analysis and Surveillance Branch; and Joyce Martin, Team Leader, Perinatal Research and Statistics Team, Statistical Analysis and Surveillance Branch. Rajesh Virkar, Chief of the Systems, Programming, and Statistical Resources Branch, and Annie S. Liu, Systems, Programming, and Statistical Resources Branch, provided computer programming support and statistical tables. Annie S. Liu also prepared the natality file. The Data Acquisition and Evaluation Branch staff evaluated the quality of and acceptance procedures for the state data files on which this report is based. The National Center for Health Statistics Office of Information Services, Information Design and Publishing Staff edited and produced this report: editor Jane Sudol and typesetter and graphic designer Ebony Davis.

## Technical Notes

### Data source

Data shown in this report for 2024 are based on 100% of the birth certificates filed in all states and the District of Columbia (D.C.). The data are provided to the National Center for Health Statistics (NCHS) through the Vital Statistics Cooperative Program. Information on the percentage of records with missing information for maternal and infant characteristics included in this report is shown by state in the “User Guide to the 2024 Natality Public Use File” (8); methodological and measurement information for these characteristics is also available in the 2024 User Guide.

#### 2003 revision of U.S. Standard Certificate of Live Birth

Data for 2016–2024 presented in this report are based on the 2003 revision of the U.S. Standard Certificate of Live Birth; data for 2010–2015 are based on both the 1989 and 2003 birth certificate revisions. The 2003 revision is described in detail elsewhere (12,24).

### Age of mother

Age of mother is computed in most cases from the mother’s and infant’s dates of birth as reported on the birth certificate. Since 2007, age of mother has been imputed for age 8 and younger and age 65 and older. Mothers age 9 are recoded as age 10. A review and verification of unedited data for several years including 2007 showed that most births reported as occurring to women age 50 and older were to women ages 50–54. In this report, the final age group shown in the tables (40–54, 45–49, 45–54, or 50–54) includes births to mothers up to age 64. For detailed and historical information on mother’s age, see the 2024 User Guide (8).

### Marital status

Due to state statutory restrictions, beginning in 2017, California no longer provides record-level data on the marital status of the mother for births occurring in, or to residents of, the state. California instead provides to NCHS counts of births by marital status category (married, unmarried, and unknown) by age and race and Hispanic origin of the mother, according to the age and race and Hispanic-origin categories shown in this report. For consistency with procedures for handling missing information for other jurisdictions, California’s counts of birth by marital status were redistributed (proportionately) to the same maternal age, race, and marital status subgroups in the data set to obtain the national estimates by marital status. This approach is consistent with hot-deck procedures used for non-California records to impute missing information for age, race, and marital status based on records for which these characteristics are known.

### Hispanic origin and race

#### Hispanic origin

Hispanic origin and race are reported separately on the birth certificate. Data are shown in most cases for five specified Hispanic groups: Central and South American, Cuban, Dominican, Mexican, and Puerto Rican, as well as other and unknown Hispanic. Before 2018, data for the Dominican subgroup had been included in the category of other and unknown Hispanic. In tabulations of birth data by race and Hispanic origin, data for people of Hispanic origin are not further classified by race because most births to Hispanic women are reported as White. Starting with 2023, data for Central and South American no longer include Latin American, which has been moved to other and unknown Hispanic to conform with the U.S. Census Bureau (8).

Items asking for the Hispanic origin of the mother (and the father) have been included on the birth certificates of all states, D.C., U.S. Virgin Islands, and Guam since 1993, and on the birth certificates of Puerto Rico starting in 2005 and Northern Mariana Islands (Northern Marianas) starting in 2010 (8,13). American Samoa does not collect information on Hispanic origin.

The Hispanic-origin question on the 2003 revision of the birth certificate asks respondents to select only one response. Occasionally, however, more than one Hispanic-origin response is given (that is, a specified Hispanic group [Central and South American, Cuban, Dominican, Mexican, or Puerto Rican] in combination with one or more other specified Hispanic groups). From 2003 to 2012, respondents who selected more than one Hispanic origin on the birth certificate were classified as “other Hispanic.” Beginning with the 2013 data year, respondents who select more than one Hispanic origin are randomly assigned to a single Hispanic origin. This change was implemented to be consistent with the coding methods of the American Community Survey (ACS) (25), on which the rates for the specified Hispanic groups from 2020 are based (see “Population estimates for specific Hispanic groups”).

#### Race

This report presents data on race and Hispanic origin based on the 1997 Office of Management and Budget (OMB) standards (14). The 2003 revision of the U.S. Standard Certificate of Live Birth allows the reporting of five race categories either alone (single race) or in combination (more than one race or multiple races) for each parent (11), according to the revised standards issued by OMB in 1997 (14). The five categories for race specified in the revised standards are: American Indian and Alaska Native, Asian, Black or African American, Native Hawaiian and Other Pacific Islander, and White; see the 2024 User Guide (8).

Beginning in 2016, all states and D.C., in addition to Puerto Rico, U.S. Virgin Islands, Guam, and Northern Marianas, were reporting race according to the 1997 revised OMB standards; American Samoa began reporting in 2019. A total of 3.0% of mothers in the United States reported more than one race in 2024 (8). Before 2016, the multiple-race reporting states varied widely, increasing from 6 states in 2003 to all 50 states, D.C., and all territories except American Samoa in 2016.

### Gestational age

Beginning with the 2014 data year, NCHS transitioned to a new standard for estimating the gestational age of the newborn. The new measure—the obstetric estimate of gestation at delivery—replaces the measure based on the date of the last normal menses (22). National data based on the obstetric estimate are available only from data year 2007 forward. Gestational age estimates differ somewhat between the obstetric estimate- and last normal menses-based measures. Accordingly, gestational age data in this report are based on the obstetric estimate. Information and discussion of the reasons for the change, and a detailed comparison of the two measures, are presented elsewhere (22).

### Computations of rates, percentages, percent distributions, and means

For information and discussion on computations of rates, percentages, percent distributions, and means, see the 2024 User Guide (8). Births for which a particular characteristic is unknown were subtracted from the counts for total births used as denominators before percentages, percentage distributions, and means were computed. The mean age of mother is the arithmetic average of the age of mothers at the time of birth, computed directly from the frequency of births by age of mother.

### Population denominators

The birth and fertility rates for 2024 shown in Tables A, 1, 2, and 6 are estimated as of July 1, 2024, based on the blended base population estimates produced by the U.S. Census Bureau instead of the April 1, 2020, decennial population count. The blended base consists of the blend of 2020 census data, 2020 Demographic Analysis estimates, and Vintage 2020 estimates (26,27). These populations are shown in the 2024 User Guide (8). The population estimates provided by the Census Bureau (28) are presented by age, sex, and race. The race categories are consistent with the revised 1997 OMB standards (14). See also the 2024 User Guide for information on population counts for the U.S. territories.

The birth and fertility rates by state shown in Table 6 are based on state population counts, which are based on the blended base population estimates provided by the Census Bureau (28). Birth and fertility rates for the territories except Puerto Rico shown in Table 6 are based on population estimates provided by the Census Bureau’s International Database (29). Rates for Puerto Rico are based on estimates developed from a base that integrates the 2020 census data and Vintage 2020 estimates, as of July 1, 2024, and are provided by the Census Bureau (30).

Rates by state and territory shown in this report may differ from rates computed based on other population estimates; rates for smaller population subgroups, such as those for teen mothers, may be particularly affected by differences in population estimates. For 2023, rates for unmarried women shown in Tables 10 and 11 are based on distributions of the population by marital status averaged over a 2-year period for 2023–2024. These distributions were reported by the Census Bureau in the March Current Population Survey (CPS) for each year (31,32) and have been adjusted to July 1, 2024, (blended base) population levels (28) by NCHS’ Division of Vital Statistics (33).

The population distributions by marital status are based on a 2-year average (of the current and previous year) from 2023 to 2024 (13). For earlier years, rates for unmarried females are based on distributions of the population by marital status averaged over a 3-year period (33).

Birth and fertility rates for 2020 have been revised and may differ from those published in “Births: Final Data for 2020” and elsewhere (16). Previously published birth and fertility rates for 2020 were based on postcensal population estimates derived from the 2010 census. The revised rates shown in this report are based on population estimates consistent with the blended base as of April 1. When the intercensal population estimates for 2011–2019 based on the blended base population estimates become available, revised birth and fertility rates for 2011–2019 will be presented in a separate report.

### Population estimates for specific Hispanic groups

The 2024 population estimates for the specific Hispanic population groups were not available when this report was being prepared (34). Accordingly, birth and fertility rates for these groups for 2024 are not shown in this report. Once available, birth and fertility rates for the specific Hispanic population groups will be published.

### Presentation of counts, rates, and percentages

An asterisk (*) in the tables indicates that a count, rate, or percentage does not meet NCHS standards of reliability (35,36). Two separate criteria are used to determine if a count (number of events), rate, or proportion meets these standards (8).

#### Presentation of counts and rates

New criteria for showing counts and rates (based on a population denominator from a decennial census or postcensal or intercensal population estimate) were adopted by NCHS beginning with 2023 data (35). The number of births or a rate is shown depending on the count of births (by itself or as the numerator of the rate) and on the relative width of the confidence interval of the count, based on a gamma distribution. For rates based on population estimates from the CPS or ACS, a rate is shown depending on the count for the numerator and on the relative width of the confidence interval of the numerator of the rate based on a Student’s t interval for the logarithm of the rate (with the variance estimated using a method supplied with CPS data). Rates published for data years before 2023 were represented by an asterisk when the numerator was fewer than 20 births; the number of births was shown regardless of the count. For detailed information on the new criteria, see “National Center for Health Statistics Data Presentation Standards for Rates and Counts” (35).

#### Presentation of percentages

For proportions (or percentages), new criteria were adopted by NCHS beginning with 2017 data, and an additional criterion was added in 2023 (36). For 2017 and later, a proportion (percentage) was shown based on the denominator size and on the absolute or relative widths of the confidence interval of the proportion or percentage calculated using the Clopper–Pearson method. For the presentation criterion used before the 2017 data year, see the 2024 User Guide (8). Starting in 2023, proportions or percentages are represented with an asterisk when the number is fewer than 10 births. For detailed information on these criteria, see “National Center for Health Statistics Data Presentation Standards for Proportions” (36).

### Random variation and significance testing for natality data

For information and discussion on random variation and significance testing for natality data, see the 2010 User Guide (37).

For information and discussion on random variation and significance testing for birth and fertility rates for Central and South American, Cuban, Dominican, Mexican, Puerto Rican, and other Hispanic populations based on ACS population estimates, see the 2024 User Guide (8).

### Definition of medical terms

For definition and discussion of medical and health items presented in this report, see “Guide to Completing the Facility Worksheets for the Certificate of Live Birth and Report of Fetal Death” (38).

## References

1 Hamilton BE, Martin JA, Osterman MJK. Births: Provisional data for 2024. Vital Statistics Rapid Release. 2025 Apr;(35):1–10. DOI: 10.15620/cdc:174587.
2 Martin JA, Hamilton BE, Osterman MJK. Births in the United States, 2024. NCHS Data Brief. 2025 Jul;(535):1–8. DOI: 10.15620/cdc:174613.
3 National Center for Health Statistics. Vital statistics online data portal: Birth data files. Available from: https://www.cdc.gov/nchs/data_access/VitalStatsOnline.htm.
4 National Center for Health Statistics. Data release policy for vital statistics micro-data files. Available from: https://www.cdc.gov/nchs/nvss/dvs_data_release.htm.
5 Centers for Disease Control and Prevention. CDC WONDER. Natality information: Live births. Available from: https://wonder.cdc.gov/natality.html.
6 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2022. Natl Vital Stat Rep. 2024 Apr;73(2):1–56. DOI: 10.15620/cdc:145588.
7 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2023. Natl Vital Stat Rep. 2025 Mar;74(1):1–87. DOI: 10.15620/cdc/175204.40570233
8 National Center for Health Statistics. User guide to the 2024 natality public use file. 2026 update. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2024.pdf.
9 Martin JA, Wilson EC, Osterman MJK, Saadi EW, Sutton SR, Hamilton BE. Assessing the quality of medical and health data from the 2003 birth certificate revision: Results from two states. Natl Vital Stat Rep. 2013 Jul;62(2):1–20. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr62/nvsr62_02.pdf.
10 Gregory ECW, Martin JA, Argov EL, Osterman MJK. Assessing the quality of medical and health data from the 2003 birth certificate revision: Results from New York City. Natl Vital Stat Rep. 2019 Jun;68(8):1–20. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr68/nvsr68_08-508.pdf.
11 National Center for Health Statistics. 2003 revisions of the U.S. standard certificates and reports. Available from: https://www.cdc.gov/nchs/nvss/vital_certificate_revisions.htm.
12 National Center for Health Statistics. Report of the Panel to Evaluate the U.S. Standard Certificates. 2000.
13 Martin JA, Hamilton BE, Osterman MJK, Driscoll AK, Mathews TJ. Births: Final data for 2015. Natl Vital Stat Rep. 2017 Jan;66(1):1–70 Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr66/nvsr66_01.pdf.
14 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist 1997;62(210):58782–90.
15 Martin JA, Hamilton BE, Osterman MJK, Driscoll AK, Drake P. Births: Final data for 2016. Natl Vital Stat Rep. 2018 Jan;67(1):1–55. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr67/nvsr67_01.pdf.
16 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2020. Natl Vital Stat Rep. 2022 Feb;70(17):1–50. DOI: 10.15620/cdc/112078.35319436
17 National Center for Health Statistics. Vital statistics of the United States, 2003, vol I, natality. Available from: https://www.cdc.gov/nchs/products/vsus/vsus_1980_2003.htm.
18 Martin JA, Osterman MJK, Driscoll AK. Declines in cigarette smoking during pregnancy in the United States, 2016–2021. NCHS Data Brief. 2023 Jan;(458):1–8. DOI: 10.15620/cdc:123360.
19 Osterman MJK, Martin JA. Changes in timing of prenatal care initiation: United States, 2021–2024. NCHS Data Brief. 2026 Feb;(550):1–11. DOI: 10.15620/cdc:174642.
20 Osterman MJK. Changes in primary and repeat cesarean delivery: United States, 2016–2021. Vital Statistics Rapid Release. 2022 Jul;(21):1–11. DOI: 10.15620/cdc:117432.
21 Valenzuela CP, Osterman MJK. Characteristics of mothers by source of payment for the delivery: United States, 2021. NCHS Data Brief. 2023 May;(468):1–8. DOI: 10.15620/cdc:127266.
22 Martin JA, Osterman MJK, Kirmeyer SE, Gregory ECW. Measuring gestational age in vital statistics data: Transitioning to the obstetric estimate. Natl Vital Stat Rep. 2015 Jun;64(5):1–20. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr64/nvsr64_05.pdf.
23 Martin JA, Osterman MJK. Shifts in the distribution of births by gestational age: United States, 2014–2022. Natl Vital Stat Rep. 2024 Jan;73(1):1–11. DOI: 10.15620/cdc:135610.
24 Hamilton BE, Martin JA, Osterman MJK, Curtin SC, Mathews TJ. Births: Final data for 2014. Natl Vital Stat Rep. 2015 Dec;64(12):1–64. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr64/nvsr64_12.pdf.
25 Ramirez RR, Ennis SR. Item nonresponse, allocation, and data editing of the question on Hispanic origin in the American Community Survey (ACS): 2000 to 2007. U.S. Census Bureau. Working Paper no 86. 2010.
26 U.S. Census Bureau. Vintage 2024 release notes. Available from: https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2024/2024-est-relnotes.pdf.
27 U.S. Census Bureau. Methodology for the United States population estimates: Vintage 2024. Nation, states, counties, and Puerto Rico–April 1, 2020 to July 1, 2024. 2025. Available from: https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2024/methods-statement-v2024.pdf.
28 U.S. Census Bureau. 2024 population estimates. Annual state resident population estimates for 6 race groups (5 race alone groups and two or more races) by age, sex, and Hispanic origin: April 1, 2020 to July 1, 2024 (SC-EST2024-ALLDATA6). 2025. Available from: https://www2.census.gov/programs-surveys/popest/datasets/2020-2024/state/asrh/sc-est2024-alldata6.csv.
29 U.S. Census Bureau. International database. Population by single years of age and sex, 2024. 2025. Available from: https://www.census.gov/data-tools/demo/idb/#/pop?dashboard_page=country&COUNTRY_YR_ANIM=2025&CCODE=**&popPages=BYAGE&menu=popViz&POP_YEARS=2024.
30 U.S. Census Bureau. 2024 population estimates. Annual estimates of the resident population by single year of age and sex for Puerto Rico Commonwealth: April 1, 2020 to July 1, 2024 (PRCEST2024-SYASEX). 2025. Available from: https://www2.census.gov/programs-surveys/popest/tables/2020-2024/puerto-rico/asrh/prc-est2024-syasex.xlsx.
31 U.S. Census Bureau. Microdata access tool. Current Population Survey. 2023 March annual social and economic supplement. 2024. Available from: https://data.census.gov/mdat/.
32 U.S. Census Bureau. Microdata access tool. Current Population Survey. 2024 March annual social and economic supplement. 2025. Available from: https://data.census.gov/mdat/.
33 Ventura SJ, Bachrach CA. Nonmarital childbearing in the United States, 1940–99. Natl Vital Stat Rep. 2000 Oct 18;48(16):1–39. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr48/nvs48_16.pdf.
34 U.S. Census Bureau. American Community Survey (ACS), 2024 1-year estimates (st31002_2024_010_flags), by sex, age, nativity, and Hispanic origin. Population estimates for 2024 based on unpublished tabulations. [Forthcoming].
35 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D, et al. National Center for Health Statistics data presentation standards for rates and counts. National Center for Health Statistics. Vital Health Stat 2. 2023 Mar;(200):1–26. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02-200.pdf.
36 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. Vital Health Stat >2. 2017 Aug;(175):1–22. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_175.pdf.
37 National Center for Health Statistics. User guide to the 2010 natality public use file. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2010.pdf.
38 National Center for Health Statistics. Guide to completing the facility worksheets for the Certificate of Live Birth and Report of Fetal Death (2003 revision). 2022. Available from: https://www.cdc.gov/nchs/data/dvs/GuidetoCompleteFacilityWks.pdf.

National Center for Health Statistics

Carolyn M. Greene, M.D., Acting Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/.

For questions or general information about NCHS: Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info