# Volume 74, Number 7 Infant Mortality in the United States, 2023: Data From the Period Linked Birth/Infant Death File

### Objectives

This report presents final 2023 infant mortality statistics by age at death, maternal race and Hispanic origin, maternal age, gestational age, leading causes of death, and maternal state of residence. Trends in infant mortality are also examined.

### Methods

Descriptive tabulations of data are presented and interpreted for infant deaths and infant mortality rates using the 2023 period linked birth/infant death file. The linked birth/infant death file is based on birth and death certificates registered in all 50 states and the District of Columbia.

### Results

A total of 20,162 infant deaths were reported in the United States in 2023, down 2% from 2022. The U.S. infant mortality rate was 5.61 infant deaths per 1,000 live births, unchanged from the rate in 2022. Changes in the neonatal mortality rate from 3.59 in 2022 to 3.65 in 2023, and in the postneonatal mortality rate from 2.02 to 1.96, were not significant. Changes in mortality rates for infants by maternal race and Hispanic-origin group were not significant; among Hispanic-origin subgroups, rates increased for infants of Mexican women in 2023 compared with 2022. Infants of Black non-Hispanic women had the highest mortality rate (10.93) in 2023, followed by infants of American Indian and Alaska Native non-Hispanic (9.20) and Native Hawaiian or Other Pacific Islander non-Hispanic (8.21), Hispanic (5.03), White non-Hispanic (4.48), and Asian non-Hispanic (3.44) women. The mortality rate decreased from 2022 to 2023 for infants born at 41 weeks of gestation (1.73 to 1.46) but were essentially unchanged for other gestational age categories. The five leading causes of infant death in 2023 were the same as in 2022. Infant mortality rates by state for 2023 ranged from a low of 2.93 in New Hampshire to a high of 8.94 in Mississippi.

## Introduction

This report presents infant mortality statistics based on data from the 2023 period linked birth/infant death file. Infant mortality and mortality rates are described by age at death, maternal race and Hispanic origin, maternal age, gestational age, leading causes of death, and maternal state of residence. Infant mortality trends are also presented by selected characteristics. In the linked file, information from the death certificate is linked to information from the birth certificate for each infant younger than age 1 year who died in the 50 states, the District of Columbia, Puerto Rico, or Guam during 2023 (1). The purpose of the linkage is to use variables available from the birth certificate to conduct more detailed analyses of infant mortality patterns (2,3). The linked birth/infant death data set also is the preferred source for examining infant mortality by race and Hispanic origin. Infant mortality rates by race and Hispanic origin, based on maternal race and Hispanic origin, are more accurately measured from the birth certificate compared with the death certificate.

For 2023, linked birth/infant death data are not available for American Samoa, Commonwealth of the Northern Marianas, and U.S. Virgin Islands. Some rates calculated from the mortality file differ from those published using the linked file. More details can be found elsewhere (1).

## Methods

Data shown in this report are based on birth and infant death certificates registered in all states, the District of Columbia, Puerto Rico, and Guam. As part of the Vital Statistics Cooperative Program, each state provides matching birth and death certificate numbers for each infant younger than age 1 year who died during 2023 to the National Center for Health Statistics. Further discussion of the process of linking births and deaths occurring in different states and file production can be found in the Methodology section of the “User Guide to the 2023 Period/2022 Cohort Linked Birth/Infant Death Public Use File” (1).

The period linked file for 2017 marked the first data year for which the linked birth data for infant deaths for all 50 states and the District of Columbia were based on the 2003 revision of the U.S. Standard Certificate of Live Birth (4) and, also, the first year for which national data on race and Hispanic-origin categories based on 1997 Office of Management and Budget standards became available (5).

In 2023, 98.8% of all infant death records were successfully linked to their corresponding birth records. These records were weighted to adjust for the 1.2% of infant death records that were not linked to their corresponding birth certificates (1) (Technical Notes).

Information for age and race of mother is imputed if it is not reported on the birth certificate. In 2023, race of mother was imputed for 8.1% of births; mother’s age was imputed for 0.02% of births (2,3).

All race and Hispanic-origin data are based on single-race reporting and are consistent with the 1997 Office of Management and Budget standards and differ from the bridged-race categories shown in previous reports (5). Maternal race and Hispanic-origin categories presented are American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native), Asian non-Hispanic (subsequently, Asian), Black non-Hispanic (subsequently, Black), Native Hawaiian or Other Pacific Islander non-Hispanic (subsequently, Native Hawaiian or Other Pacific Islander), White non-Hispanic (subsequently, White), and Hispanic. Race and Hispanic origin are reported separately on the birth certificate. Data are shown in most cases for five specified Hispanic groups: Central and South American, Cuban, Dominican, Mexican, and Puerto Rican. Additional details on Hispanic origin are available elsewhere (3). Comparisons between 2023 and 2022 by race and Hispanic origin are made in this report. The 2003 revision of the U.S. Standard Certificate of Live Birth allows the reporting of five race categories for each parent (6)—either alone, as in single race, or in combination, as in more than one race or multiple races—in accordance with the 1997 revised Office of Management and Budget standards (5). Further details on race reporting are available elsewhere (3).

Cause-of-death statistics are classified in accordance with the International Statistical Classification of Diseases and Related Health Problems, 10th Revision (ICD–10) (7) (Technical Notes).

### Data by maternal and infant characteristics

This report presents descriptive tabulations of infant mortality data by a variety of maternal and infant characteristics. These tabulations are useful for understanding the basic relationships between risk factors and infant mortality, unadjusted for the possible effects of other variables. This report also presents several key risk factors for infant mortality: age at death, maternal race and Hispanic origin, maternal age, gestational age, leading causes of infant death, and maternal state of residence. For brevity, additional selected risk factors (sex, birthweight, plurality, and nativity [mother’s place of birth]) are presented in tables but not discussed in this report.

Race and Hispanic origin—Infant mortality rates are presented by race and Hispanic origin of the mother. The linked file is useful for computing accurate infant mortality rates by these characteristics because the race and Hispanic origin of the mother from the birth certificate are used in both the numerator and denominator of the infant mortality rate. In contrast, for rates based on the vital statistics mortality file, race information for the denominator is the race of the mother as reported on the birth certificate, while race information for the numerator is the race of the decedent as reported on the death certificate (2,3,8). More detail on the reliability of race and Hispanic-origin data from the linked file compared with the mortality file is available elsewhere (8).

Statistical significance—Statements in the text have been tested for statistical significance, and a statement that a given infant mortality rate is higher or lower than another rate indicates that the rates are significantly different using a two-tailed z test at the alpha level of 0.05. Comparisons between state rates and the U.S. rate take into account each state’s contribution to the U.S. rate. As a result, each state rate is compared with a unique U.S. rate independent of the state’s contribution to the total U.S. rate. Information on the methods used to test for statistical significance and suppression standards, as well as information on differences between period and cohort data, the weighting of the linked file, maternal age, period of gestation, birthweight, and cause-of-death classification is also available (1) (Technical Notes).

## Results

### Trends in infant mortality and infant age at death

- In 2023, 20,162 infant deaths were reported in the United States, a decrease of 2% from 2022 (20,577) (Figure 1, Table 1). The infant mortality rate was 5.61 deaths per 1,000 live births in 2023, unchanged from the 2022 rate; the increase in the rate from 2021 (5.44) to 2022 was the first since the increase from 2001 (6.84) to 2002 (6.95).
- The U.S. infant mortality rate has generally trended downward since 1995 (the first year that the period linked birth/infant death file was available) and is down 19% since 2002.
- The 2023 neonatal mortality rate (infant deaths at less than 28 days) of 3.65 was not significantly different than the rate in 2022 (3.59); the increase in the rate from 2021 (3.49) to 2022 was the first since the increase from 2001 (4.54) to 2002 (4.67). The neonatal mortality rate has generally declined since 1995 and decreased 22% since the last increase in 2002.
- The 2023 postneonatal mortality rate (infant deaths at 28 days or more) of 1.96 was essentially unchanged from the rate in 2022 (2.02). The rate increased from 2021 (1.95) to 2022. The postneonatal mortality rate has also generally declined since 1995 and decreased 14% since 2002 (2.28).

Figure 1

Infant, neonatal, and postneonatal mortality rates: United States, 1995–2023

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 1 is a line graph showing infant, neonatal, and postneonatal mortality rates in the United States, 1995–2023.

Table 1

Live births; infant, neonatal, and postneonatal deaths; and mortality rate: United States, 1995–2023, and by maternal race and Hispanic origin, 2017–2023

Race and Hispanic origin and year | Number | | | | Deaths per 1,000 live births
Race and Hispanic origin and year | Live births | Infant deaths | Neonatal deaths | Postneonatal deaths | Infant | Neonatal | Postneonatal
All race and Hispanic-origin groups
2023 | 3,596,017 | 20,162 | 13,113 | 7,049 | 5.61 | 3.65 | 1.96
2022 | 3,667,758 | 20,577 | 13,158 | 7,419 | 5.61 | 3.59 | 2.02
2021 | 3,664,292 | 19,928 | 12,797 | 7,131 | 5.44 | 3.49 | 1.95
2020 | 3,613,647 | 19,578 | 12,866 | 6,712 | 5.42 | 3.56 | 1.86
2019 | 3,747,540 | 20,927 | 13,834 | 7,093 | 5.58 | 3.69 | 1.89
2018 | 3,791,712 | 21,498 | 14,329 | 7,169 | 5.67 | 3.78 | 1.89
2017 | 3,855,500 | 22,341 | 14,844 | 7,497 | 5.79 | 3.85 | 1.94
2016 | 3,945,875 | 23,157 | 15,303 | 7,854 | 5.87 | 3.88 | 1.99
2015 | 3,978,497 | 23,458 | 15,672 | 7,786 | 5.90 | 3.94 | 1.96
2014 | 3,988,076 | 23,211 | 15,737 | 7,474 | 5.82 | 3.95 | 1.87
2013 | 3,932,181 | 23,446 | 15,893 | 7,553 | 5.96 | 4.04 | 1.92
2012 | 3,952,841 | 23,654 | 15,887 | 7,767 | 5.98 | 4.02 | 1.96
2011 | 3,953,590 | 24,001 | 16,065 | 7,936 | 6.07 | 4.06 | 2.01
2010 | 3,999,386 | 24,572 | 16,193 | 8,379 | 6.14 | 4.05 | 2.10
2009 | 4,130,665 | 26,408 | 17,261 | 9,148 | 6.39 | 4.18 | 2.21
2008 | 4,247,726 | 28,075 | 18,238 | 9,837 | 6.61 | 4.29 | 2.32
2007 | 4,316,233 | 29,153 | 19,094 | 10,059 | 6.75 | 4.42 | 2.33
2006 | 4,265,593 | 28,509 | 19,041 | 9,468 | 6.68 | 4.46 | 2.22
2005 | 4,138,573 | 28,384 | 18,782 | 9,602 | 6.86 | 4.54 | 2.32
2004 | 4,112,055 | 27,860 | 18,602 | 9,258 | 6.78 | 4.52 | 2.25
2003 | 4,090,007 | 27,995 | 18,935 | 9,060 | 6.84 | 4.63 | 2.22
2002 | 4,021,825 | 27,970 | 18,791 | 9,179 | 6.95 | 4.67 | 2.28
2001 | 4,026,036 | 27,523 | 18,275 | 9,248 | 6.84 | 4.54 | 2.30
2000 | 4,058,882 | 27,961 | 18,733 | 9,227 | 6.89 | 4.62 | 2.27
1999 | 3,959,417 | 27,865 | 18,701 | 9,164 | 7.04 | 4.72 | 2.31
1998 | 3,941,553 | 28,325 | 18,915 | 9,410 | 7.19 | 4.80 | 2.39
1997 | 3,880,894 | 27,968 | 18,507 | 9,461 | 7.21 | 4.77 | 2.44
1996 | 3,891,494 | 28,419 | 18,556 | 9,863 | 7.30 | 4.77 | 2.53
1995 | 3,899,589 | 29,505 | 19,186 | 10,319 | 7.57 | 4.92 | 2.65
Non-Hispanic, single race
American Indian and Alaska Native:
2023 | 24,571 | 226 | 117 | 108 | 9.20 | 4.76 | 4.40
2022 | 25,721 | 233 | 135 | 98 | 9.06 | 5.25 | 3.81
2021 | 26,124 | 195 | 100 | 96 | 7.46 | 3.83 | 3.67
2020 | 26,813 | 206 | 102 | 104 | 7.68 | 3.80 | 3.88
2019 | 28,450 | 224 | 114 | 110 | 7.87 | 4.01 | 3.87
2018 | 29,092 | 237 | 120 | 117 | 8.15 | 4.12 | 4.02
2017 | 29,957 | 276 | 143 | 132 | 9.21 | 4.77 | 4.41
Asian:
2023 | 215,738 | 742 | 542 | 199 | 3.44 | 2.51 | 0.92
2022 | 218,994 | 768 | 542 | 225 | 3.51 | 2.47 | 1.03
2021 | 213,813 | 788 | 594 | 193 | 3.69 | 2.78 | 0.90
2020 | 219,068 | 688 | 503 | 185 | 3.14 | 2.30 | 0.84
2019 | 238,769 | 806 | 602 | 204 | 3.38 | 2.52 | 0.85
2018 | 240,798 | 874 | 643 | 231 | 3.63 | 2.67 | 0.96
2017 | 249,250 | 943 | 675 | 268 | 3.78 | 2.71 | 1.08
Black:
2023 | 491,494 | 5,374 | 3,260 | 2,114 | 10.93 | 6.63 | 4.30
2022 | 511,439 | 5,573 | 3,296 | 2,277 | 10.90 | 6.44 | 4.45
2021 | 517,889 | 5,463 | 3,291 | 2,172 | 10.55 | 6.35 | 4.19
2020 | 529,811 | 5,501 | 3,472 | 2,028 | 10.38 | 6.55 | 3.83
2019 | 548,075 | 5,821 | 3,754 | 2,067 | 10.62 | 6.85 | 3.77
2018 | 552,029 | 5,933 | 3,897 | 2,037 | 10.75 | 7.06 | 3.69
2017 | 560,715 | 6,152 | 4,012 | 2,140 | 10.97 | 7.16 | 3.82
Native Hawaiian or Other Pacific Islander:
2023 | 10,115 | 83 | 50 | 33 | 8.21 | 4.94 | 3.26
2022 | 10,122 | 86 | 48 | 38 | 8.50 | 4.74 | 3.75
2021 | 9,531 | 74 | 41 | 32 | 7.76 | 4.30 | 3.36
2020 | 9,626 | 69 | 41 | 27 | 7.17 | 4.26 | 2.80
2019 | 9,770 | 80 | 49 | 31 | 8.19 | 5.02 | 3.17
2018 | 9,476 | 89 | 51 | 38 | 9.39 | 5.38 | 4.01
2017 | 9,426 | 72 | 36 | 36 | 7.64 | 3.82 | 3.82
White:
2023 | 1,787,051 | 8,008 | 5,127 | 2,881 | 4.48 | 2.87 | 1.61
2022 | 1,840,739 | 8,324 | 5,318 | 3,006 | 4.52 | 2.89 | 1.63
2021 | 1,887,656 | 8,236 | 5,251 | 2,984 | 4.36 | 2.78 | 1.58
2020 | 1,843,432 | 8,115 | 5,290 | 2,825 | 4.40 | 2.87 | 1.53
2019 | 1,915,912 | 8,603 | 5,589 | 3,014 | 4.49 | 2.92 | 1.57
2018 | 1,956,413 | 9,059 | 5,873 | 3,186 | 4.63 | 3.00 | 1.63
2017 | 1,992,461 | 9,306 | 6,061 | 3,246 | 4.67 | 3.04 | 1.63
Hispanic
2023 | 945,200 | 4,750 | 3,356 | 1,394 | 5.03 | 3.55 | 1.47
2022 | 937,421 | 4,581 | 3,138 | 1,442 | 4.89 | 3.35 | 1.54
2021 | 885,916 | 4,246 | 2,899 | 1,347 | 4.79 | 3.27 | 1.52
2020 | 866,713 | 4,063 | 2,828 | 1,235 | 4.69 | 3.26 | 1.42
2019 | 886,467 | 4,462 | 3,091 | 1,371 | 5.03 | 3.49 | 1.55
2018 | 886,210 | 4,303 | 3,036 | 1,267 | 4.86 | 3.43 | 1.43
2017 | 898,764 | 4,583 | 3,198 | 1,383 | 5.10 | 3.56 | 1.54
Central and South American:
2023 | 208,618 | 958 | 697 | 261 | 4.59 | 3.34 | 1.25
2022 | 207,843 | 907 | 652 | 255 | 4.36 | 3.14 | 1.23
2021 | 178,067 | 748 | 521 | 227 | 4.20 | 2.93 | 1.27
2020 | 169,811 | 659 | 470 | 189 | 3.88 | 2.77 | 1.11
2019 | 165,229 | 749 | 535 | 214 | 4.53 | 3.24 | 1.30
2018 | 147,430 | 592 | 438 | 154 | 4.02 | 2.97 | 1.04
2017 | 145,614 | 653 | 465 | 188 | 4.48 | 3.19 | 1.29
Cuban:
2023 | 30,001 | 113 | 86 | 27 | 3.77 | 2.87 | 0.90
2022 | 26,390 | 104 | 65 | 39 | 3.94 | 2.46 | 1.48
2021 | 24,437 | 87 | 68 | 19 | 3.56 | 2.78 | *
2020 | 23,188 | 98 | 63 | 34 | 4.23 | 2.72 | 1.47
2019 | 23,668 | 98 | 65 | 33 | 4.14 | 2.75 | 1.39
2018 | 23,471 | 90 | 64 | 26 | 3.83 | 2.73 | 1.11
2017 | 23,362 | 93 | 69 | 24 | 3.98 | 2.95 | 1.03
Dominican:
2023 | 33,575 | 154 | 106 | 48 | 4.59 | 3.16 | 1.43
2022 | 33,531 | 159 | 112 | 46 | 4.74 | 3.34 | 1.37
2021 | 33,373 | 109 | 68 | 41 | 3.27 | 2.04 | 1.23
2020 | 31,596 | 143 | 101 | 42 | 4.53 | 3.20 | 1.33
2019 | 32,483 | 153 | 111 | 42 | 4.71 | 3.42 | 1.29
Mexican:
2023 | 508,127 | 2,601 | 1,845 | 757 | 5.12 | 3.63 | 1.49
2022 | 510,194 | 2,442 | 1,688 | 754 | 4.79 | 3.31 | 1.48
2021 | 485,127 | 2,380 | 1,633 | 747 | 4.91 | 3.37 | 1.54
2020 | 480,531 | 2,264 | 1,586 | 678 | 4.71 | 3.30 | 1.41
2019 | 496,716 | 2,462 | 1,693 | 769 | 4.96 | 3.41 | 1.55
2018 | 495,831 | 2,426 | 1,690 | 736 | 4.89 | 3.41 | 1.48
2017 | 512,126 | 2,588 | 1,795 | 792 | 5.05 | 3.50 | 1.55
Puerto Rican:
2023 | 66,203 | 426 | 282 | 144 | 6.43 | 4.26 | 2.18
2022 | 69,266 | 438 | 267 | 171 | 6.32 | 3.85 | 2.47
2021 | 70,729 | 428 | 278 | 151 | 6.05 | 3.93 | 2.13
2020 | 69,763 | 437 | 308 | 129 | 6.26 | 4.41 | 1.85
2019 | 70,950 | 438 | 294 | 144 | 6.17 | 4.14 | 2.03
2018 | 71,614 | 402 | 290 | 112 | 5.61 | 4.05 | 1.56
2017 | 70,813 | 459 | 307 | 151 | 6.48 | 4.34 | 2.13

* Estimate does not meet National Center for Health Statistics standards of reliability.

NOTES: People of Hispanic origin may be of any race. Infant deaths are weighted to adjust for the 1.1% of infant death records not linked to their corresponding birth certificates. The neonatal and postneonatal mortality rates combined may not exactly add to totals due to rounding. Data for infants of Dominican women are available starting with the 2019 period linked birth/infant death data files.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Race and Hispanic origin

- Mortality rates did not change significantly from 2022 to 2023 for infants of women of any of the race and Hispanic-origin groups: American Indian and Alaska Native (9.06 infant deaths per 1,000 live births in 2022 to 9.20 in 2023), Asian (3.51 to 3.44), Black (10.90 to 10.93), Native Hawaiian and Other Pacific Islander (8.50 to 8.21), White (4.52 to 4.48), and Hispanic (4.89 to 5.03) (Tables 1 and 2, Figure 2).
- Among Hispanic-origin subgroups, the mortality rate for infants of Mexican women increased from 4.79 to 5.12 from 2022 to 2023; increases in mortality rates for infants of Central and South American (4.36 to 4.59) and Puerto Rican (6.32 to 6.43) women were not significant. Declines in mortality rates for infants of Cuban (3.94 to 3.77) and Dominican (4.74 to 4.59) women from 2022 to 2023 were not significant.
- In 2023, infant mortality continued to vary by race: infants of Black women had the highest mortality rate (10.93), followed by infants of American Indian and Alaska Native and Native Hawaiian or Other Pacific Islander (9.20 and 8.21, respectively), Hispanic (5.03), White (4.48), and Asian (3.44) women.
- Infants of Black women also had the highest neonatal mortality rate in 2023 (6.63) compared with infants of the other race and Hispanic-origin groups; the lowest mortality rate was for infants of Asian women (2.51) (Table 2).
- In 2023, postneonatal mortality rates were higher for infants of American Indian and Alaska Native (4.40), Black (4.30), and Native Hawaiian or Other Pacific Islander (3.26) women than for infants of White (1.61), Hispanic (1.47), and Asian (0.92) women.
- Among Hispanic-origin subgroups in 2023, the mortality rate for infants of Puerto Rican women (6.43) was higher than that of infants of Mexican (5.12), Dominican (4.59), Central and South American (4.59), and Cuban (3.77) women.

Figure 2

Infant mortality rate, by maternal race and Hispanic origin: United States, 2022 and 2023

^1^People of Hispanic origin may be of any race.

NOTE: There were no significant differences in rates between 2022 and 2023.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 2 is a bar graph showing infant mortality rate by maternal race and Hispanic origin in the United States for 2022 and 2023.

Table 2

Infant mortality rate, live births, and infant deaths, by selected characteristics and maternal race and Hispanic origin: United States, 2023

Characteristic | Total | Non-Hispanic | | | | | Hispanic
Characteristic | Total | American Indian and Alaska Native^1^ | Asian | Black | Native Hawaiian or Other Pacific Islander | White | Total^2^ | Central andSouth American | Cuban | Dominican | Mexican | Puerto Rican
| Infant deaths per 1,000 live births in specified group
Total | 5.61 | 9.20 | 3.44 | 10.93 | 8.21 | 4.48 | 5.03 | 4.59 | 3.77 | 4.59 | 5.12 | 6.43
Age at death (days)
Total neonatal | 3.65 | 4.76 | 2.51 | 6.63 | 4.94 | 2.87 | 3.55 | 3.34 | 2.87 | 3.16 | 3.63 | 4.26
Early neonatal (less than 7) | 2.84 | 3.78 | 1.90 | 5.14 | 3.95 | 2.22 | 2.83 | 2.73 | 2.17 | 2.38 | 2.88 | 3.26
Late neonatal (7–27) | 0.80 | 0.98 | 0.61 | 1.49 | 0.99 | 0.65 | 0.72 | 0.61 | 0.70 | 0.77 | 0.76 | 1.00
Postneonatal (28–364) | 1.96 | 4.40 | 0.92 | 4.30 | 3.26 | 1.61 | 1.47 | 1.25 | 0.90 | 1.43 | 1.49 | 2.18
Sex
Male | 6.04 | 10.32 | 3.77 | 11.56 | 7.67 | 4.89 | 5.40 | 5.01 | 4.29 | 5.26 | 5.46 | 6.80
Female | 5.15 | 7.96 | 3.08 | 10.28 | 8.75 | 4.05 | 4.64 | 4.15 | 3.28 | 3.93 | 4.76 | 6.06
Period of gestation (weeks)
Less than 37 | 34.74 | 39.67 | 25.68 | 51.16 | 34.02 | 28.38 | 33.89 | 33.03 | 28.68 | 32.29 | 34.81 | 36.09
Less than 34 | 107.87 | 125.51 | 89.71 | 130.35 | 110.09 | 92.96 | 110.29 | 115.83 | 98.70 | 101.43 | 111.54 | 107.32
Less than 28 | 362.14 | 410.40 | 332.10 | 360.63 | 333.33 | 364.49 | 355.51 | 369.96 | 315.27 | 334.66 | 358.19 | 359.17
28–31 | 43.40 | * | 26.91 | 45.26 | * | 41.85 | 46.33 | 58.94 | 42.02 | 37.27 | 43.39 | 37.88
32–33 | 21.04 | 40.88 | 18.31 | 23.75 | * | 19.67 | 21.12 | 19.60 | * | * | 24.13 | 20.97
34–36 | 8.31 | 11.51 | 4.10 | 11.87 | * | 7.81 | 7.28 | 6.18 | * | 4.87 | 8.17 | 7.52
37–41 | 2.16 | 4.80 | 1.20 | 3.87 | 4.20 | 1.95 | 1.73 | 1.53 | 1.07 | 1.43 | 1.77 | 2.42
37–38 | 3.22 | 5.87 | 1.74 | 5.02 | 6.96 | 3.13 | 2.42 | 2.15 | 2.02 | 2.01 | 2.53 | 3.11
39–40 | 1.64 | 4.36 | 0.91 | 3.19 | 2.69 | 1.41 | 1.40 | 1.21 | 0.57 | 1.17 | 1.41 | 2.08
41 | 1.46 | * | * | 2.32 | * | 1.43 | 1.11 | 1.40 | * | * | 0.95 | *
42 or more | 3.66 | * | * | * | * | 3.47 | * | * | * | * | * | *
Birthweight (grams)
Less than 2,500 | 42.33 | 53.50 | 25.72 | 51.35 | 48.63 | 37.77 | 43.83 | 44.69 | 39.22 | 36.48 | 46.00 | 40.29
Less than 1,500 | 196.71 | 234.10 | 162.63 | 203.80 | 208.86 | 186.60 | 203.73 | 222.55 | 180.66 | 169.74 | 208.61 | 188.25
1,500–2,499 | 12.72 | 18.49 | 6.43 | 14.03 | 15.23 | 12.61 | 12.94 | 12.79 | 7.89 | 7.60 | 14.47 | 10.09
2,500 or more | 2.10 | 4.86 | 1.09 | 3.78 | 4.04 | 1.93 | 1.64 | 1.35 | 1.01 | 1.41 | 1.68 | 2.45
2,500–4,499 | 2.10 | 4.89 | 1.08 | 3.75 | 4.11 | 1.93 | 1.64 | 1.35 | 1.02 | 1.42 | 1.67 | 2.45
4,500 or more | 2.46 | * | * | 7.84 | * | 1.77 | 2.14 | * | * | * | * | *
Plurality
Single births | 5.09 | 8.75 | 3.23 | 9.83 | 7.93 | 4.09 | 4.57 | 4.16 | 3.02 | 4.15 | 4.67 | 6.06
Twin births | 20.78 | 23.95 | 11.13 | 34.50 | * | 15.45 | 22.13 | 24.06 | 29.31 | 17.47 | 22.34 | 15.41
Triplet and higher-order births | 52.39 | * | * | 85.98 | * | 41.91 | 52.34 | * | * | * | 53.85 | *
Age of mother | Infant deaths per 1,000 live births in specified group—Con.
Younger than 15 | 20.95 | * | * | 30.86 | * | * | 12.50 | * | * | * | * | *
15–19 | 10.44 | 11.95 | * | 15.87 | * | 10.86 | 7.15 | 5.93 | * | * | 6.81 | 11.58
20–24 | 7.23 | 10.98 | 5.94 | 12.82 | 8.66 | 6.18 | 5.53 | 4.41 | 4.98 | 4.91 | 5.65 | 7.01
25–29 | 5.24 | 7.89 | 3.99 | 10.18 | 5.61 | 4.23 | 4.44 | 4.14 | 3.25 | 5.27 | 4.48 | 5.60
30–34 | 4.59 | 8.54 | 2.97 | 9.70 | 7.06 | 3.58 | 4.47 | 4.46 | 4.24 | 3.99 | 4.42 | 6.04
35–39 | 4.94 | 6.80 | 3.14 | 9.60 | 11.42 | 3.98 | 5.10 | 4.70 | 2.75 | 3.90 | 5.51 | 6.02
40–54 | 6.77 | * | 4.26 | 11.73 | * | 5.73 | 6.38 | 6.05 | * | * | 7.23 | 5.19
Mother’s place of birth
50 states or District of Columbia | 5.80 | 9.10 | 3.48 | 11.54 | 8.68 | 4.54 | 5.11 | 4.46 | 4.06 | 3.85 | 5.00 | 6.21
Elsewhere | 4.76 | * | 3.43 | 7.91 | 7.67 | 3.31 | 4.90 | 4.62 | 3.61 | 4.89 | 5.30 | 6.82
| Live births
Total | 3,596,017 | 24,571 | 215,738 | 491,494 | 10,115 | 1,787,051 | 945,200 | 208,618 | 30,001 | 33,575 | 508,127 | 66,203
Sex
Male | 1,839,794 | 12,505 | 111,542 | 249,931 | 5,087 | 916,170 | 482,254 | 106,726 | 15,378 | 17,309 | 258,596 | 33,848
Female | 1,756,223 | 12,066 | 104,196 | 241,563 | 5,028 | 870,881 | 462,946 | 101,892 | 14,623 | 16,266 | 249,531 | 32,355
Period of gestation (weeks)
Less than 37 | 373,902 | 3,000 | 19,587 | 71,956 | 1,264 | 168,654 | 95,755 | 19,922 | 2,929 | 3,438 | 51,134 | 7,814
Less than 34 | 99,255 | 741 | 4,938 | 23,859 | 327 | 40,736 | 24,735 | 4,869 | 770 | 976 | 13,179 | 2,227
Less than 28 | 23,096 | 173 | 1,081 | 7,046 | 84 | 7,789 | 5,966 | 1,165 | 203 | 251 | 3,191 | 529
28–31 | 33,153 | 250 | 1,672 | 7,887 | 100 | 13,523 | 8,354 | 1,561 | 238 | 322 | 4,517 | 792
32–33 | 43,006 | 318 | 2,185 | 8,926 | 143 | 19,424 | 10,415 | 2,143 | 329 | 403 | 5,471 | 906
34–36 | 274,647 | 2,259 | 14,649 | 48,097 | 937 | 127,918 | 71,020 | 15,053 | 2,159 | 2,462 | 37,955 | 5,587
37–41 | 3,210,174 | 21,474 | 195,957 | 418,212 | 8,807 | 1,611,436 | 847,391 | 188,191 | 27,024 | 30,108 | 455,922 | 58,289
37–38 | 1,072,092 | 8,181 | 68,461 | 164,390 | 3,162 | 505,444 | 287,252 | 61,968 | 8,414 | 9,926 | 155,613 | 20,598
39–40 | 1,974,300 | 12,372 | 120,557 | 237,042 | 5,213 | 1,013,077 | 520,655 | 116,923 | 17,459 | 18,836 | 279,216 | 35,085
41 | 163,782 | 921 | 6,939 | 16,780 | 432 | 92,915 | 39,484 | 9,300 | 1,151 | 1,346 | 21,093 | 2,606
42 or more | 9,299 | 49 | 140 | 1,028 | 27 | 6,050 | 1,607 | 389 | 43 | 26 | 873 | 87
Not stated | 2,642 | 48 | 54 | 298 | 17 | 911 | 447 | 116 | * | * | 198 | 13
Birthweight (grams)
Less than 2,500 | 309,391 | 2,131 | 20,414 | 73,007 | 946 | 126,063 | 75,133 | 15,395 | 2,167 | 3,043 | 39,194 | 6,925
Less than 1,500 | 49,799 | 346 | 2,521 | 14,357 | 158 | 18,226 | 12,163 | 2,341 | 393 | 542 | 6,366 | 1,174
1,500–2,499 | 259,592 | 1,785 | 17,893 | 58,650 | 788 | 107,837 | 62,970 | 13,054 | 1,774 | 2,501 | 32,828 | 5,751
2,500 or more | 3,285,678 | 22,434 | 195,312 | 418,407 | 9,167 | 1,660,812 | 870,006 | 193,202 | 27,834 | 30,532 | 468,904 | 59,276
2,500–4,499 | 3,253,557 | 22,076 | 194,495 | 415,983 | 8,999 | 1,640,988 | 862,531 | 191,758 | 27,539 | 30,329 | 464,565 | 58,810
4,500 or more | 32,121 | 358 | 817 | 2,424 | 168 | 19,824 | 7,475 | 1,444 | 295 | 203 | 4,339 | 466
Not stated | 948 | * | 12 | 80 | * | 176 | 61 | 21 | * | * | 29 | *
Plurality | Live births—Con.
Single births | 3,482,971 | 23,899 | 210,328 | 470,612 | 9,842 | 1,729,043 | 921,711 | 204,219 | 29,129 | 32,555 | 495,738 | 64,045
Twin births | 110,393 | 668 | 5,300 | 20,347 | 270 | 56,648 | 22,954 | 4,323 | 853 | 973 | 12,129 | 2,076
Triplet and higher-order births | 2,653 | * | 110 | 535 | * | 1,360 | 535 | 76 | 19 | 47 | 260 | 82
Age of mother
Younger than 15 | 1,766 | 23 | * | 486 | * | 351 | 800 | 304 | * | 12 | 356 | 30
15–19 | 140,977 | 1,841 | 925 | 28,414 | 459 | 44,922 | 57,914 | 14,324 | 639 | 1,198 | 31,865 | 3,800
20–24 | 616,970 | 6,285 | 9,420 | 103,077 | 2,424 | 263,760 | 207,702 | 42,377 | 4,816 | 6,116 | 117,437 | 15,415
25–29 | 986,567 | 6,843 | 40,837 | 131,705 | 3,031 | 500,910 | 270,317 | 56,021 | 8,314 | 9,301 | 149,457 | 19,476
30–34 | 1,098,052 | 5,970 | 88,489 | 131,500 | 2,409 | 595,741 | 240,489 | 52,706 | 9,659 | 10,013 | 125,796 | 16,884
35–39 | 604,631 | 2,942 | 60,802 | 74,492 | 1,401 | 314,198 | 131,623 | 32,976 | 5,447 | 5,388 | 65,363 | 8,477
40–54 | 147,054 | 667 | 15,258 | 21,820 | 389 | 67,169 | 36,355 | 9,910 | 1,122 | 1,547 | 17,853 | 2,121
Mother’s place of birth
50 states or District of Columbia | 2,744,794 | 24,183 | 51,139 | 396,282 | 3,458 | 1,662,528 | 503,410 | 34,084 | 10,583 | 10,386 | 329,614 | 47,987
Elsewhere | 843,233 | 349 | 164,063 | 93,217 | 6,521 | 121,879 | 440,349 | 174,323 | 19,401 | 23,092 | 178,031 | 17,880
Not stated | 7,990 | 39 | 536 | 1,995 | 136 | 2,644 | 1,441 | 211 | 17 | 97 | 482 | 336
| Infant deaths
Total | 20,162 | 226 | 742 | 5,374 | 83 | 8,008 | 4,750 | 958 | 113 | 154 | 2,601 | 426
Age at death
Total neonatal | 13,113 | 117 | 542 | 3,260 | 50 | 5,127 | 3,356 | 697 | 86 | 106 | 1,845 | 282
Early neonatal (less than 7 days) | 10,226 | 93 | 410 | 2,526 | 40 | 3,961 | 2,672 | 569 | 65 | 80 | 1,461 | 216
Late neonatal (7–27 days) | 2,887 | 24 | 132 | 734 | 10 | 1,166 | 683 | 128 | 21 | 26 | 384 | 66
Postneonatal | 7,049 | 108 | 199 | 2,114 | 33 | 2,881 | 1,394 | 261 | 27 | 48 | 757 | 144
Sex
Male | 11,118 | 129 | 421 | 2,890 | 39 | 4,482 | 2,604 | 535 | 66 | 91 | 1,412 | 230
Female | 9,044 | 96 | 321 | 2,484 | 44 | 3,526 | 2,146 | 423 | 48 | 64 | 1,189 | 196
Period of gestation (weeks)
Less than 37 | 12,990 | 119 | 503 | 3,681 | 43 | 4,786 | 3,245 | 658 | 84 | 111 | 1,780 | 282
Less than 34 | 10,707 | 93 | 443 | 3,110 | 36 | 3,787 | 2,728 | 564 | 76 | 99 | 1,470 | 239
Less than 28 | 8,364 | 71 | 359 | 2,541 | 28 | 2,839 | 2,121 | 431 | 64 | 84 | 1,143 | 190
28–31 | 1,439 | * | 45 | 357 | * | 566 | 387 | 92 | 10 | 12 | 196 | 30
32–33 | 905 | 13 | 40 | 212 | * | 382 | 220 | 42 | * | * | 132 | 19
34–36 | 2,282 | 26 | 60 | 571 | * | 999 | 517 | 93 | * | 12 | 310 | 42
37–41 | 6,932 | 103 | 235 | 1,619 | 37 | 3,140 | 1,468 | 287 | 29 | 43 | 807 | 141
37–38 | 3,450 | 48 | 119 | 825 | 22 | 1,582 | 695 | 133 | 17 | 20 | 393 | 64
39–40 | 3,242 | 54 | 110 | 755 | 14 | 1,424 | 729 | 141 | 10 | 22 | 394 | 73
41 | 239 | * | * | 39 | * | 133 | 44 | 13 | * | * | 20 | *
42 or more | 34 | – | – | * | – | 21 | * | – | – | – | * | *
Not stated | 206 | * | * | 68 | * | 62 | 33 | 13 | – | – | 13 | *
Birthweight (grams) | Infant deaths—Con.
Less than 2,500 | 13,098 | 114 | 525 | 3,749 | 46 | 4,761 | 3,293 | 688 | 85 | 111 | 1,803 | 279
Less than 1,500 | 9,796 | 81 | 410 | 2,926 | 33 | 3,401 | 2,478 | 521 | 71 | 92 | 1,328 | 221
1,500–2,499 | 3,301 | 33 | 115 | 823 | 12 | 1,360 | 815 | 167 | 14 | 19 | 475 | 58
2,500 or more | 6,916 | 109 | 213 | 1,582 | 37 | 3,200 | 1,431 | 261 | 28 | 43 | 787 | 145
2,500–4,499 | 6,837 | 108 | 210 | 1,562 | 37 | 3,165 | 1,415 | 259 | 28 | 43 | 778 | 144
4,500 or more | 79 | * | * | 19 | – | 35 | 16 | * | – | – | * | *
Not stated | 148 | * | * | 43 | – | 46 | 25 | * | – | – | 11 | *
Plurality
Single births | 17,728 | 209 | 679 | 4,626 | 78 | 7,076 | 4,214 | 849 | 88 | 135 | 2,315 | 388
Twin births | 2,294 | 16 | 59 | 702 | * | 875 | 508 | 104 | 25 | 17 | 271 | 32
Triplet and higher-order births | 139 | - | * | 46 | - | 57 | 28 | * | - | * | 14 | *
Age of mother
Younger than 15 | 37 | * | – | 15 | – | * | 10 | * | – | – | * | –
15–19 | 1,472 | 22 | * | 451 | * | 488 | 414 | 85 | – | * | 217 | 44
20–24 | 4,459 | 69 | 56 | 1,321 | 21 | 1,629 | 1,148 | 187 | 24 | 30 | 663 | 108
25–29 | 5,170 | 54 | 163 | 1,341 | 17 | 2,118 | 1,201 | 232 | 27 | 49 | 670 | 109
30–34 | 5,040 | 51 | 263 | 1,275 | 17 | 2,133 | 1,074 | 235 | 41 | 40 | 556 | 102
35–39 | 2,988 | 20 | 191 | 715 | 16 | 1,250 | 671 | 155 | 15 | 21 | 360 | 51
40–54 | 996 | * | 65 | 256 | * | 385 | 232 | 60 | * | * | 129 | 11
Mother’s place of birth
50 states or District of Columbia | 15,914 | 220 | 178 | 4,575 | 30 | 7,545 | 2,572 | 152 | 43 | 40 | 1,649 | 298
Elsewhere | 4,018 | * | 562 | 737 | 50 | 404 | 2,156 | 805 | 70 | 113 | 944 | 122
Not stated | 229 | * | * | 63 | * | 59 | 22 | * | - | * | * | *

* Figure does not meet National Center for Health Statistics standards of reliability.

– Quantity zero.

^1^Includes Aleut and Eskimo people.

^2^Includes other and unknown Hispanic origin not stated and not shown separately.

NOTES: Infant deaths are weighted so numbers may not exactly add to totals due to rounding. Not stated responses were included in totals but not distributed among groups for rate computations. Race and Hispanic origin are reported separately on birth certificates. Race categories are consistent with the 1997 Office of Management and Budget standards. People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Maternal age

- From 2022 to 2023, no significant changes in mortality rates for infants of women of any age group were seen (Figure 3, Table 2).
- Nonsignificant increases in mortality rates were seen for infants of females younger than age 15 (14.25 infant deaths per 1,000 live births to 20.95) and ages 15–19 (9.86 to 10.44), and for infants of women ages 20–24 (7.13 to 7.23) and 40 and older (6.73 to 6.77).
- Decreases in mortality rates for infants of women ages 25–29 (5.37 to 5.24) and 35–39 (4.99 to 4.94) were not significant. The rate for infants of women ages 30–34 was unchanged from 2022 to 2023 at 4.59.
- In 2023, mortality rates were highest for infants of females younger than 15 (20.95), decreased to a low of 4.59 for infants of women ages 30–34, and then increased to 6.77 for infants of women age 40 and older.

Figure 3

Infant mortality rate, by maternal age: United States, 2022 and 2023

NOTE: There were no significant differences in rates between 2022 and 2023.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 3 is a bar graph showing infant mortality rate by maternal age in the United States for 2022 and 2023.

### Gestational age

- The mortality rate declined for infants born at 41 weeks (1.73 infant deaths per 1,000 live births to 1.46) but did not change significantly for the other gestational age categories from 2022 to 2023: preterm (less than 37 weeks of gestation) (34.78 to 34.74), early preterm (less than 34 weeks) (107.94 to 107.87), late preterm (34–36 weeks) (8.29 to 8.31), term (37–41 weeks) (2.18 to 2.16), and post-term (42 weeks or more) (4.23 to 3.66) (9) (Table, Table 2).
- In 2023, almost two-thirds of all infant deaths (65%) occurred among infants born preterm (less than 37 weeks of gestation), which was unchanged from 2022 (9).

Table

Infant mortality rate, by gestational age: United States, 2015–2023

Year | Less than 32 weeks | 32–33 weeks | 34–36 weeks | 37–41 weeks | 42 weeks or more
| Deaths per 1,000 live births
2023 | 174.28 | 21.04 | 8.31 | 2.16 | 3.66
2022 | 175.18 | 21.05 | 8.29 | 2.18 | 4.23
2021 | 167.39 | 19.35 | 8.11 | 2.08 | 3.79
2020 | 175.88 | 20.11 | 7.92 | 2.04 | 4.17
2019 | 180.40 | 19.21 | 8.21 | 2.03 | 5.72
2018 | 185.79 | 21.95 | 8.21 | 2.05 | 5.39
2017 | 187.56 | 20.50 | 8.50 | 2.10 | 3.98
2016 | 190.15 | 20.12 | 8.65 | 2.19 | 4.31
2015 | 193.54 | 20.79 | 8.76 | 2.17 | 4.20

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Leading causes of infant death

- In 2023, the five leading causes of all infant deaths were the same as those in 2022: congenital malformations (20.0% of infant deaths), disorders related to short gestation and low birth weight (14.5%), sudden infant death syndrome (SIDS) (7.2%), unintentional injuries (6.4%), and maternal complications (5.7%) (Table 3).
- From 2022 to 2023, no significant changes in infant mortality rates were seen for the five leading causes of death: congenital malformations (from 109.2 infant deaths per 100,000 live births to 112.1), disorders related to short gestation and low birth weight (78.6 to 81.4), SIDS (41.7 to 40.2), unintentional injuries (36.8 to 35.8), and maternal complications (33.1 to 31.9).
- Congenital malformations was the leading cause of death for infants of women for most race and Hispanic-origin groups: American Indian and Alaska Native (134.3), Asian (69.1), Native Hawaiian and Other Pacific Islander (148.3), White (102.2), and Hispanic (119.6) in 2023 (Table 4).
- In 2023, disorders related to short gestation and low birth weight was the leading cause of death for infants of Black women (201.0).

Table 3

Infant deaths, percentage of deaths, and infant mortality rate, by five leading causes of infant death: United States, 2010–2023

Year | Congenital malformations(Q00–Q99) | | | Short gestation and low birthweight,not elsewhere classified (P07) | | | Sudden infant death syndrome(R95) | | | Accidents (unintentional injuries)(V01–X59) | | | Maternal complications of pregnancy (P01)
Year | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births)
2023 | 4,030 | 20.0 | 112.1 | 2,927 | 14.5 | 81.4 | 1,446 | 7.2 | 40.2 | 1,288 | 6.4 | 35.8 | 1,146 | 5.7 | 31.9
2022 | 4,004 | 19.5 | 109.2 | 2,884 | 14.0 | 78.6 | 1,531 | 7.4 | 41.7 | 1,351 | 6.6 | 36.8 | 1,213 | 5.9 | 33.1
2021 | 3,990 | 20.0 | 108.9 | 2,957 | 14.8 | 80.7 | 1,458 | 7.3 | 39.8 | 1,300 | 6.5 | 35.5 | 1,113 | 5.6 | 30.4
2020 | 4,047 | 20.7 | 112.0 | 3,152 | 16.1 | 87.2 | 1,386 | 7.1 | 38.4 | 1,192 | 6.1 | 33.0 | 1,115 | 5.7 | 30.9
2019 | 4,313 | 20.6 | 115.1 | 3,460 | 16.5 | 92.3 | 1,251 | 6.0 | 33.4 | 1,264 | 6.0 | 33.7 | 1,250 | 6.0 | 33.4
2018 | 4,501 | 20.9 | 118.7 | 3,683 | 17.1 | 97.1 | 1,331 | 6.2 | 35.1 | 1,169 | 5.4 | 30.8 | 1,371 | 6.4 | 36.2
2017 | 4,596 | 20.6 | 119.2 | 3,757 | 16.8 | 97.4 | 1,360 | 6.1 | 35.3 | 1,313 | 5.9 | 34.1 | 1,436 | 6.4 | 37.2
2016 | 4,823 | 20.8 | 122.2 | 3,926 | 17.0 | 99.5 | 1,498 | 6.5 | 38.0 | 1,217 | 5.3 | 30.8 | 1,407 | 6.1 | 35.7
2015 | 4,847 | 20.7 | 121.8 | 4,087 | 17.4 | 102.7 | 1,567 | 6.7 | 39.4 | 1,289 | 5.5 | 32.4 | 1,527 | 6.5 | 38.4
2014 | 4,754 | 20.5 | 119.2 | 4,172 | 18.0 | 104.6 | 1,541 | 6.6 | 38.6 | 1,163 | 5.0 | 29.2 | 1,580 | 6.8 | 39.6
2013 | 4,778 | 20.4 | 121.5 | 4,213 | 18.0 | 107.1 | 1,561 | 6.7 | 39.7 | 1,150 | 4.9 | 29.2 | 1,597 | 6.8 | 40.6
2012 | 4,967 | 21.0 | 125.7 | 4,214 | 17.8 | 106.6 | 1,676 | 7.1 | 42.4 | 1,163 | 4.9 | 29.4 | 1,518 | 6.4 | 38.4
2011 | 5,016 | 20.9 | 126.9 | 4,115 | 17.1 | 104.1 | 1,905 | 7.9 | 48.2 | 1,167 | 4.9 | 29.5 | 1,598 | 6.7 | 40.4
2010 | 5,115 | 20.8 | 127.9 | 4,151 | 16.9 | 103.8 | 2,058 | 8.4 | 51.5 | 1,107 | 4.5 | 27.7 | 1,563 | 6.4 | 39.1

NOTE: The five leading causes of death (based on International Classification of Diseases, 10th Revision, 1992) were the same for 2010–2023, but ranking changed in 2020 and later years compared with previous years.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Table 4

Infant deaths and mortality rate for the five leading causes of infant death, by maternal race and Hispanic origin: United States, 2023

[Rates are per 100,000 live births in specified group]

Cause of death (based onInternational Classification of Diseases, 10th Revision, 1992) | All races | | | Non-Hispanic
Cause of death (based onInternational Classification of Diseases, 10th Revision, 1992) | All races | | | American Indian andAlaska Native | | | Asian^1^ | | | Black | | | Native Hawaiian or Other Pacific Islander | | | White
Cause of death (based onInternational Classification of Diseases, 10th Revision, 1992) | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate
All causes | … | 20,162 | 560.7 | … | 226 | 919.8 | … | 742 | 343.9 | … | 5,374 | 1,093.4 | … | 83 | 820.6 | … | 8,008 | 448.1
Congenital malformations,deformations, and chromosomal abnormalities (Q00–Q99) | 1 | 4,030 | 112.1 | 1 | 33 | 134.3 | 1 | 149 | 69.1 | 2 | 720 | 146.5 | 1 | 15 | 148.3 | 1 | 1,827 | 102.2
Disorders related to short gestationand low birth weight, not elsewhere classified(P07) | 2 | 2,927 | 81.4 | 3 | 23 | 93.6 | 2 | 116 | 53.8 | 1 | 988 | 201.0 | … | * | * | 2 | 873 | 48.9
Sudden infant death syndrome(R95) | 3 | 1,446 | 40.2 | 2 | 24 | 97.7 | 6 | 21 | 9.7 | 3 | 464 | 94.4 | 2 | 13 | 128.5 | 3 | 609 | 34.1
Accidents (unintentionalinjuries)(V01–X59) | 4 | 1,288 | 35.8 | 4 | 21 | 85.5 | 7 | 18 | 8.3 | 4 | 393 | 80.0 | … | * | * | 4 | 572 | 32.0
Newborn affected by maternalcomplications of pregnancy(P01) | 5 | 1,146 | 31.9 | 5 | 13 | 52.9 | 3 | 55 | 25.5 | 5 | 306 | 62.3 | … | * | * | 5 | 383 | 21.4
Cause of death (based onInternational Classification of Diseases, 10th Revision, 1992) | Total Hispanic | | | Central and South American^2^ | | | Cuban | | | Dominican^3^ | | | Mexican | | | Puerto Rican
Cause of death (based onInternational Classification of Diseases, 10th Revision, 1992) | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate
All causes | … | 4,750 | 502.5 | … | 958 | 459.2 | … | 113 | 376.7 | … | 154 | 458.7 | … | 2,601 | 511.9 | … | 426 | 643.5
Congenital malformations,deformations, and chromosomal abnormalities (Q00–Q99) | 1 | 1,130 | 119.6 | 1 | 268 | 128.5 | 2 | 20 | 66.7 | 2 | 22 | 65.5 | 1 | 644 | 126.7 | 2 | 67 | 101.2
Disorders related to short gestationand low birth weight, not elsewhere classified(P07) | 2 | 755 | 79.9 | 2 | 171 | 82.0 | 1 | 29 | 96.7 | 1 | 28 | 83.4 | 2 | 381 | 75.0 | 1 | 73 | 110.3
Sudden infant death syndrome(R95) | 4 | 223 | 23.6 | 4 | 37 | 17.7 | … | * | * | 3 | 13 | 38.7 | 5 | 114 | 22.4 | 4 | 28 | 42.3
Accidents (unintentionalinjuries)(V01–X59) | 5 | 208 | 22.0 | 7 | 30 | 14.4 | … | * | * | … | * | * | 4 | 123 | 24.2 | 5 | 26 | 39.3
Newborn affected by maternalcomplications of pregnancy(P01) | 3 | 310 | 32.8 | 3 | 53 | 25.4 | … | * | * | 4 | 11 | 32.8 | 3 | 167 | 32.9 | 3 | 34 | 51.4

… Category not applicable.

* Figure does not meet National Center for Health Statistics standards of reliability.

^1^For infants born to Asian non-Hispanic women, Complications of placenta, cord and membranes (P02) was the fourth leading cause of death, with 36 deaths and a rate of 16.7. Bacterial sepsis (P36.9) was the fifth leading cause of death, with 26 deaths and a rate of 12.1.

^2^For infants born to Central and South American women, Bacterial sepsis (P36.9) was the fifth leading cause of death, with 33 deaths and a rate of 15.8.

^3^For infants born to Dominican women, Bacterial sepsis (P36.9) was tied for fourth leading cause of death, with 11 deaths and a rate of 32.8.

NOTES: Certain cause-specific infant mortality rates and rankings cannot be shown for infants of Native Hawaiian or Other Pacific Islander non-Hispanic, Cuban, or Dominican women because of the small number of infant deaths. Race and Hispanic origin are reported separately on birth certificates. Race categories are consistent with the 1997 Office of Management and Budget standards. People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Infant mortality by state

- By state, infant mortality ranged from a low of 2.93 infant deaths per 1,000 births in New Hampshire to a high of 8.94 in Mississippi (Figure 4, Table 5).
- Thirteen states had infant mortality rates significantly lower than the national infant mortality rate: California, Colorado, Connecticut, Idaho, Massachusetts, Minnesota, New Hampshire, New Jersey, New Mexico, New York, Oregon, Vermont, and Washington.
- Fourteen states had infant mortality rates significantly higher than the U.S. infant mortality rate: Alabama, Arkansas, Florida, Georgia, Indiana, Kentucky, Louisiana, Michigan, Mississippi, North Carolina, Ohio, Oklahoma, South Carolina, and Tennessee.

Figure 4

Infant mortality rate, by state: United States, 2023

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 4 is a U.S. map showing infant mortality rate by state in the United States for 2023.

Table 5

Infant mortality rate: United States and each state, 2023

[By place of residence]

Area | Rate (deaths per 1,000 births) | Infant deaths | Live births
United States^1^ | 5.61 | 20,162 | 3,596,017
Alabama | 7.64 | 442 | 57,858
Alaska | 7.21 | 65 | 9,015
Arizona | 5.54 | 433 | 78,096
Arkansas | 8.22 | 290 | 35,264
California | 4.10 | 1,642 | 400,108
Colorado | 4.55 | 280 | 61,494
Connecticut | 4.49 | 155 | 34,559
Delaware | 6.14 | 64 | 10,427
District of Columbia | 6.97 | 55 | 7,896
Florida | 6.10 | 1,351 | 221,410
Georgia | 6.99 | 874 | 125,120
Hawaii | 4.86 | 72 | 14,808
Idaho | 4.38 | 98 | 22,397
Illinois | 5.91 | 738 | 124,820
Indiana | 6.51 | 514 | 79,000
Iowa | 5.10 | 184 | 36,052
Kansas | 5.23 | 178 | 34,065
Kentucky | 6.58 | 342 | 51,984
Louisiana | 7.14 | 392 | 54,927
Maine | 5.68 | 66 | 11,627
Maryland | 5.61 | 368 | 65,594
Massachusetts | 3.28 | 220 | 67,093
Michigan | 6.09 | 604 | 99,124
Minnesota | 4.73 | 292 | 61,715
Mississippi | 8.94 | 308 | 34,459
Missouri | 6.12 | 411 | 67,123
Montana | 5.51 | 61 | 11,078
Nebraska | 6.39 | 154 | 24,111
Nevada | 5.88 | 187 | 31,794
New Hampshire | 2.93 | 35 | 11,936
New Jersey | 3.69 | 373 | 101,001
New Mexico | 4.39 | 92 | 20,951
New York | 4.03 | 821 | 203,612
North Carolina | 6.95 | 834 | 120,082
North Dakota | 4.87 | 47 | 9,647
Ohio | 7.16 | 909 | 126,896
Oklahoma | 7.12 | 341 | 47,909
Oregon | 4.62 | 177 | 38,298
Pennsylvania | 5.57 | 707 | 126,951
Rhode Island | 4.79 | 47 | 9,805
South Carolina | 6.96 | 402 | 57,729
South Dakota | 6.34 | 71 | 11,201
Tennessee | 6.48 | 538 | 83,021
Texas | 5.83 | 2,263 | 387,945
Utah | 5.22 | 235 | 45,019
Vermont | 3.16 | 16 | 5,065
Virginia | 5.87 | 544 | 92,649
Washington | 5.04 | 408 | 80,932
West Virginia | 5.60 | 93 | 16,606
Wisconsin | 5.77 | 345 | 59,754
Wyoming | 3.84 | 23 | 5,990
Puerto Rico | 7.10 | 132 | 18,601
Guam | 15.30 | 36 | 2,353

^1^Does not include Puerto Rico or Guam.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

## Acknowledgments

This report was prepared by the Division of Vital Statistics (DVS) under the general direction of DVS Director Paul Sutton; Robert Anderson, Chief, Statistical Analysis and Surveillance Branch; and Joyce Martin, Team Leader, Perinatal Research and Statistics Team, Statistical Analysis and Surveillance Branch. Rajesh Virkar, Chief of the Information Technology Branch (ITB), and Steve J. Steimel, Annie S. Liu, and Prameela Sathunuru of ITB provided computer programming support. Steve J. Steimel and Annie S. Liu prepared the natality file; Annie S. Liu and Prameela Sathunuru prepared the linked birth/infant death data file. The Data Acquisition, Classification, and Evaluation Branch staff of DVS evaluated the quality of and acceptance procedures for the state data files on which this report is based. The National Center for Health Statistics Office of Information Services, Information Design and Publishing Staff, edited and produced this report: editor Laura Drescher and typesetter and graphic designer Simon McCann.

## Technical Notes

### Data source and 2003 revision

Information on the data source for the linked birth/infant death file is available elsewhere (1). Additionally, further information on the 2003 revision of the birth certificate is available (3); see also the U.S. Standard Certificate of Live Birth (10).

### Weighting

In 2023, a record weight was added to the U.S. linked file to compensate for the 1.2% of infant death records that could not be linked to their corresponding birth certificates. The percentage of records linked varied by registration area, ranging from 93.8% through 100.0% (Table I). The number of infant deaths in the linked file for the 50 states and the District of Columbia was weighted to equal the sum of the linked plus unlinked infant deaths by state of occurrence of birth and age at death (younger than 7 days, 7–27 days, and 28 days to younger than 1 year). The addition of the weight reduced the potential for bias in comparing infant mortality rates by maternal and infant characteristics.

Table I

Percentage of infant deaths linked to their corresponding birth records, by state of occurrence of death: United States and each state, 2023

Area | Percent linked by state of occurrence of death
United States | 98.8
Alabama | 100.0
Alaska | 96.7
Arizona | 98.6
Arkansas | 100.0
California | 98.2
Colorado | 100.0
Connecticut | 100.0
Delaware | 100.0
District of Columbia | 99.2
Florida | 100.0
Georgia | 99.4
Hawaii | 98.5
Idaho | 100.0
Illinois | 99.6
Indiana | 99.8
Iowa | 100.0
Kansas | 100.0
Kentucky | 98.4
Louisiana | 97.2
Maine | 100.0
Maryland | 99.4
Massachusetts | 100.0
Michigan | 99.3
Minnesota | 100.0
Mississippi | 99.6
Missouri | 99.8
Montana | 100.0
Nebraska | 98.1
Nevada | 99.5
New Hampshire | 100.0
New Jersey | 97.4
New Mexico | 93.8
New York | 97.6
New York City | 99.5
North Carolina | 98.0
North Dakota | 100.0
Ohio | 99.7
Oklahoma | 99.7
Oregon | 99.5
Pennsylvania | 99.2
Rhode Island | 100.0
South Carolina | 100.0
South Dakota | 100.0
Tennessee | 100.0
Texas | 95.4
Utah | 100.0
Vermont | 100.0
Virginia | 98.6
Washington | 100.0
West Virginia | 97.8
Wisconsin | 99.4
Wyoming | 100.0

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

The 2023 linked file initially included 20,192 infant death records. Of these records, 19,947 were linked; 245 were unlinked because corresponding birth certificates could not be identified. The 20,192 linked and unlinked records contained 28 records of infants whose mothers’ usual place of residence was outside of the United States; these records were excluded from linked file analyses for a weighted total of 20,162 infant deaths by place of residence for 2023.

### Comparison of infant mortality data between linked file and vital statistics mortality file

The overall infant mortality rate of 5.61 from the 2023 period linked file is statistically the same as that from the 2023 vital statistics mortality file (5.60) (11). The number of infant deaths in the linked file (19,947) differs slightly from the number in the mortality file (20,145) (11). Differences in numbers of infant deaths between the two data sources are primarily due to geographic coverage differences. For the vital statistics mortality file, all deaths occurring in the 50 states and the District of Columbia are included regardless of the place of birth of the infant. In contrast, to be included in the U.S. linked file, both the birth and death must occur in the 50 states or the District of Columbia (the territory linked file is a separate file). Weighting of the linked file also may contribute to small differences in numbers and rates by specific variables between these two data sets.

### Period of gestation

Beginning with the 2014 data year, the National Center for Health Statistics (NCHS) transitioned to a new standard for estimating the gestational age of the newborn. The new measure—the obstetric estimate of gestation at delivery—replaces the measure based on the date of the last normal menses (12). Accordingly, gestational age data shown in this report are based on the obstetric estimate of gestation at delivery. National data based on obstetric estimate of gestation at delivery data are available only from data year 2007 forward. Information on and discussion of the reasons for the change, as well as a detailed comparison of the two measures, are presented elsewhere (12).

### Sex, birthweight, plurality, and nativity

Detailed definitions and more information on sex, birthweight, plurality, and nativity are available elsewhere (1,3).

### Cause-of-death classification

The mortality statistics presented in this report were compiled in accordance with the current revision of the International Statistical Classification of Diseases (ICD). ICD provides the basic guidance to code and classify causes of death, details disease classification, and supplies definitions, tabulation lists, the format of the death certificate, and the rules for coding cause of death. Cause-of-death data presented in this report were coded by procedures outlined in annual issues of the NCHS Instruction Manual (13,14).

In this report, tabulations of cause-of-death statistics are based solely on the underlying cause of death. Generally, more medical information is reported on death certificates than is directly reflected in the underlying cause of death. This is captured in NCHS multiple cause-of-death statistics (15,16).

### Tabulation lists and cause-of-death ranking

The cause-of-death rankings for ICD–10 are based on the “List of 130 Selected Causes of Infant Death.” The tabulation lists and rules for ranking leading causes of death are published in the NCHS Instruction Manual, Part 9: “ICD–10 Cause-of-death Lists for Tabulating Mortality Statistics” (17).

### Computation of rates

Information on and discussion of computation of rates (1) is also available from the “User Guide to the 2010 Natality Public Use File” at: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2010.pdf.

### Presentation of counts, rates, and percentages

An asterisk (*) in the tables indicates that a count, rate, or percentage does not meet NCHS standards of reliability (18,19). Three separate criteria are used to determine if a count (number of events), rate, or proportion meets these suppression standards (3).

#### Presentation of counts and rates

New criteria for showing counts and rates were adopted by NCHS beginning with 2023 data (18). For counts, the number of deaths is shown depending on the count of deaths and on the relative width of the confidence interval of the count, based on a gamma distribution. Before the 2023 data year, the number of deaths was shown regardless of the count. For rates, if a rate is shown depends on the count for the numerator and on the relative width of the confidence interval of the rate based on a Student’s t confidence interval for the logarithm of the rate. Rates published for data years before 2023 were represented by an asterisk when the numerator was fewer than 20 deaths. For detailed information on the new criteria, see “National Center for Health Statistics Data Presentation Standards for Rates and Counts” (18).

#### Presentation of percentages

For proportions (or percentages) for linked birth/infant deaths, new criteria adopted by NCHS were implemented starting with the 2023 data year (19). For 2023 and later, a proportion (percentage) was shown based on the denominator size and on the absolute or relative widths of the confidence interval of the proportion or percentage calculated using the Clopper–Pearson method. For the presentation criterion used before the 2023 data year, see the 2023 Natality User Guide (3). Starting in 2023, proportions or percentages based on fewer than 10 infant deaths are represented with an asterisk. For detailed information on these criteria, see “National Center for Health Statistics Data Presentation Standards for Proportions” (19).

### Random variation in infant mortality rates

For information and discussion on random variation and significance testing for linked data (1), see also the “User Guide to the 2010 Natality Public Use File” at: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2010.pdf.

### Availability of linked file

Linked file data are available for download from the Vital Statistics Online Data Portal: https://www.cdc.gov/nchs/data_access/vitalstatsonline.htm. Linked period file data may also be accessed via the Centers for Disease Control and Prevention’s WONDER database, available from: https://wonder.cdc.gov/lbd.html. Beginning with 2005, the public-use file no longer includes geographic detail; such files are available upon special request (see the NCHS Division of Vital Statistics data release policy at: https://www.cdc.gov/nchs/nvss/nvss-restricted-data.htm). Data are also available in issues of Vital and Health Statistics, Series 20; National Vital Statistics Reports; and NCHS Data Briefs from the NCHS website: https://www.cdc.gov/nchs/products/index.htm.

## References

1 National Center for Health Statistics. User guide to the 2023 period/2022 cohort linked birth/infant death public use file. 2025. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/period-cohort-linked/23PE22CO_linkedUG.pdf.
2 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2023. National Vital Statistics Reports; vol 74 no 1. Hyattsville, MD: National Center for Health Statistics. 2025. DOI: 10.15620/cdc/175204.
3 National Center for Health Statistics. User guide to the 2023 natality public use file. 2024. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2023.pdf.
4 Ely DM, Driscoll AK. Infant mortality in the United States, 2017: Data from the period linked birth/infant death file. Natl Vital Stat Rep. 2019 Aug;68(10):1–20. PMID: 32501205.
5 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist 62(210):58782–90. 1997.
6 National Center for Health Statistics. 2003 revisions of the U.S. Standard Certificates and Reports. 2003. Available from: https://www.cdc.gov/nchs/nvss/vital_certificate_revisions.htm.
7 World Health Organization. International statistical classification of diseases and related health problems, 10th Revision, Volume 2, Instruction manual, 2010 edition. World Health Organization; 2010.
8 Kochanek KD, Murphy SL, Xu J, Arias E. Deaths: Final data for 2017. Natl Vital Stat Rep. 2019 Jun;68(9):1–77. PMID: 32501199.
9 Ely DM, Driscoll AK. Infant mortality in the United States, 2022: Data from the period linked birth/infant death file. Natl Vital Stat Rep. 2024 Jul 25;(5):1–19. DOI: 10.15620/cdc/157006. PMID: 39412861; PMCID: PMC11513748.
10 National Center for Health Statistics. U.S. Standard Certificate of Live Birth. 2003. Available from: https://www.cdc.gov/nchs/data/dvs/birth11-03final-ACC.pdf.
11 Kochanek KD, Murphy SL, Xu JQ, Arias E. Deaths: Final data for 2023. National Vital Statistics Reports. Hyattsville, MD: National Center for Health Statistics. [Forthcoming].
12 Martin JA, Osterman MJ, Kirmeyer SE, Gregory EC. Measuring gestational age in vital statistics data: Transitioning to the obstetric estimate. Natl Vital Stat Rep. 2015 Jun 1;64(5):1–20. PMID: 26047089.
13 National Center for Health Statistics. Instructions for classifying the underlying cause of death, 2022. NCHS Instruction Manual, part 2a. 2022.
14 National Center for Health Statistics. Vital statistics ICD–10 ACME decision tables for classifying underlying causes of death, 2016. NCHS Instruction Manual, part 2c. 2016.
15 National Center for Health Statistics. Mortality multiple cause-of-death public use data file documentation (published annually). 2024.
16 World Health Organization. Manual of the International Statistical Classification of Diseases, Injuries and Causes of Death: Based on the recommendations of the Ninth Revision Conference, 1975, and adopted by the Twenty-ninth World Health Assembly, 1975 revision. 1977.
17 National Center for Health Statistics. ICD–10 cause-of-death lists for tabulating mortality statistics. Updated October 2020. NCHS Instruction Manual, part 9. 2020.
18 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D, Das B, Hamilton BE, Kochanek K. National Center for Health Statistics data presentation standards for rates and counts. Vital Health Stat 2. 2023 Mar;(200):1–26. DOI: 10.15620/cdc:124368.
19 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF, et al. National Center for Health Statistics data presentation standards for proportions. Vital Health Stat 2. 2017 Aug;(175): 1–22. PMID: 30248016.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/.

For questions or general information about NCHS: Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info