# Volume 74 Number 1 Births: Final Data for 2023

### Objectives

This report presents 2023 data on U.S. births by selected characteristics. Trends in fertility patterns and maternal and infant characteristics are described.

### Methods

Descriptive tabulations based on birth certificates of the 3.60 million births registered in 2023 are shown for various maternal demographic and health characteristics; medical and healthcare utilization, including source of payment for the delivery; and infant health characteristics. Selected data by mother's state of residence and birth rates also are shown. Trends for 2010 to 2023 are presented for selected items, and by race and Hispanic origin for 2016–2023.

### Results

A total of 3,596,017 births occurred in the United States in 2023, down 2% from 2022. The general fertility rate declined 3% from 2022 to 54.5 births per 1,000 females ages 15–44 in 2023. The birth rate for females ages 15–19 declined 4% from 2022 to 2023; birth rates rose less than 1% for women ages 20–24, fell 1% to 3% for women ages 25–44, and were unchanged for females ages 10–14 and women ages 45–49. The total fertility rate declined 2% to 1,621.0 births per 1,000 women in 2023. Birth rates declined for both unmarried and married women from 2022 to 2023. Prenatal care beginning in the first trimester declined to 76.1% in 2023; the percentage of women who smoked during pregnancy declined to 3.0%. The cesarean delivery rate increased 1% in 2023 to 32.3%; Medicaid was the source of payment for 41.5% of births, an increase from 2022 (41.3%). The preterm birth rate (10.41%) and the low birthweight rate for 2023 (8.58%) were essentially unchanged from 2022. The twin birth rate declined 2% in 2023 to 30.7 per 1,000 births; the triplet and higher-order multiple birth rate decreased 6% to 73.8 per 100,000 births.

## Introduction

This report presents detailed data on numbers and characteristics of births in 2023; birth and fertility rates; maternal demographic and health characteristics; medical and healthcare utilization, including source of payment for the delivery; and infant health characteristics. Reports on provisional birth statistics for 2023 that present overall and monthly data on selected topics are based on a sample of nearly all 2023 births (99.94%) (1,2); an NCHS Data Brief presented selected characteristics based on final data for 2023 births (3).

In addition to the tabulations included in this report, more detailed analysis is possible by using the annual natality public-use file. The data file may be downloaded from: https://www.cdc.gov/nchs/data_access/Vitalstatsonline.htm (4). The public-use file does not include geographic detail; a file with this information may be available by request (5). Birth data may also be accessed through the Centers for Disease Control and Prevention’s (CDC) CDC WONDER, a user-friendly web-based data query system that makes several CDC information resources available to public health professionals and the public (6).

### 2003 revision of U.S. Standard Certificate of Live Birth

Starting in 2016, all 50 states, the District of Columbia (D.C.), Puerto Rico, Guam, Commonwealth of the Northern Marianas (Northern Marianas), and U.S. Virgin Islands reported data based on the 2003 U.S. Certificate of Live Birth. American Samoa started reporting data based on the revised certificate in 2019.

Detailed tables on many topics are included in this report. Technical Notes tables on several additional topics, such as births by attendant and place of delivery, mean age of mother by live-birth order, maternal prepregnancy body mass index, infections during pregnancy, and maternal morbidity, are also available; see Tables I–XXI. For information on data quality, see reports that assessed the quality of selected medical and health data from the 2003 revised birth certificate and the “User Guide to the 2023 Natality Public Use File” (7–9).

Table I Births, by attendant, place of delivery, and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin of mother and place of delivery | All births | Physician | | | Midwife | | | Other | Unspecified
Race and Hispanic origin of mother and place of delivery | All births | Total | Doctor of medicine | Doctor of osteopathy | Total | Certified nurse midwife or certified midwife | Other midwife | Other | Unspecified
All races and origins^1^
Total | 3,596,017 | 3,096,842 | 2,739,690 | 357,152 | 454,434 | 408,214 | 46,220 | 42,490 | 2,251
In hospital^2^ | 3,512,697 | 3,094,131 | 2,737,298 | 356,833 | 390,218 | 383,846 | 6,372 | 27,445 | 903
Not in hospital | 83,172 | 2,663 | 2,350 | 313 | 64,195 | 24,357 | 39,838 | 14,991 | 1,323
Freestanding birthing center | 23,131 | 319 | 306 | 13 | 21,053 | 11,272 | 9,781 | 1,733 | 26
Clinic or doctor's office | 421 | 64 | 56 | * | 324 | 241 | 83 | 30 | *
Residence | 55,266 | 1,567 | 1,386 | 181 | 41,220 | 12,357 | 28,863 | 11,549 | 930
Other | 4,354 | 713 | 602 | 111 | 1,598 | 487 | 1,111 | 1,679 | 364
Not specified | 148 | 48 | 42 | * | 21 | 11 | 10 | 54 | 25
Non-Hispanic, single race^3^
Black:
Total | 491,494 | 432,982 | 395,691 | 37,291 | 52,218 | 49,752 | 2,466 | 5,915 | 379
In hospital^2^ | 485,302 | 432,253 | 395,022 | 37,231 | 48,968 | 48,180 | 788 | 3,920 | 161
Not in hospital | 6,152 | 708 | 651 | 57 | 3,249 | 1,571 | 1,678 | 1,980 | 215
Freestanding birthing center | 1,585 | 37 | 37 | * | 1,418 | 867 | 551 | 122 | *
Clinic or doctor's office | 30 | 14 | 13 | * | 13 | * | 10 | * | *
Residence | 4,012 | 521 | 477 | 44 | 1,747 | 656 | 1,091 | 1,588 | 156
Other | 525 | 136 | 124 | 12 | 71 | 45 | 26 | 267 | 51
Not specified | 40 | 21 | 18 | * | * | * | * | 15 | *
White:
Total | 1,787,051 | 1,511,961 | 1,309,855 | 202,106 | 250,743 | 215,907 | 34,836 | 23,394 | 953
In hospital^2^ | 1,724,954 | 1,510,655 | 1,308,710 | 201,945 | 200,146 | 196,785 | 3,361 | 13,820 | 333
Not in hospital | 62,040 | 1,292 | 1,131 | 161 | 50,584 | 19,116 | 31,468 | 9,551 | 613
Freestanding birthing center | 17,162 | 246 | 238 | * | 15,574 | 8,560 | 7,014 | 1,328 | 14
Clinic or doctor's office | 327 | 27 | 20 | * | 291 | 224 | 67 | * | *
Residence | 41,913 | 676 | 587 | 89 | 33,349 | 9,979 | 23,370 | 7,448 | 440
Other | 2,638 | 343 | 286 | 57 | 1,370 | 353 | 1,017 | 767 | 158
Not specified | 57 | 14 | 14 | * | 13 | * | * | 23 | *
Hispanic^4^
Total | 945,200 | 829,057 | 745,901 | 83,156 | 106,420 | 100,772 | 5,648 | 9,110 | 613
In hospital^2^ | 936,562 | 828,612 | 745,524 | 83,088 | 100,340 | 98,610 | 1,730 | 7,301 | 309
Not in hospital | 8,624 | 439 | 372 | 67 | 6,077 | 2,161 | 3,916 | 1,805 | 303
Freestanding birthing center | 2,788 | 20 | 17 | * | 2,585 | 1,166 | 1,419 | 179 | *
Clinic or doctor's office | 29 | 14 | 14 | * | 12 | * | * | * | *
Residence | 5,164 | 253 | 218 | 35 | 3,397 | 946 | 2,451 | 1,319 | 195
Other | 643 | 152 | 123 | 29 | 83 | 41 | 42 | 305 | 103
Not specified | 14 | * | * | * | * | * | * | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

2 Includes births occurring en route to or on arrival at hospital.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table II Births occurring at home, by state: United States and each state, 2023

[By place of residence]

Area | Number | Percent
United States | 55,266 | 1.5
Alabama | 489 | 0.8
Alaska | 273 | 3.0
Arizona | 1,157 | 1.5
Arkansas | 576 | 1.6
California | 3,701 | 0.9
Colorado | 1,187 | 1.9
Connecticut | 257 | 0.7
Delaware | 124 | 1.2
District of Columbia | 77 | 1.0
Florida | 2,833 | 1.3
Georgia | 1,360 | 1.1
Hawaii | 510 | 3.4
Idaho | 1,043 | 4.7
Illinois | 1,162 | 0.9
Indiana | 1,680 | 2.1
Iowa | 862 | 2.4
Kansas | 678 | 2.0
Kentucky | 1,116 | 2.1
Louisiana | 155 | 0.3
Maine | 320 | 2.8
Maryland | 815 | 1.2
Massachusetts | 537 | 0.8
Michigan | 2,024 | 2.0
Minnesota | 1,154 | 1.9
Mississippi | 271 | 0.8
Missouri | 1,692 | 2.5
Montana | 431 | 3.9
Nebraska | 118 | 0.5
Nevada | 601 | 1.9
New Hampshire | 270 | 2.3
New Jersey | 545 | 0.5
New Mexico | 329 | 1.6
New York | 3,045 | 1.5
North Carolina | 1,155 | 1.0
North Dakota | 174 | 1.8
Ohio | 2,289 | 1.8
Oklahoma | 624 | 1.3
Oregon | 1,048 | 2.7
Pennsylvania | 4,181 | 3.3
Rhode Island | 70 | 0.7
South Carolina | 874 | 1.5
South Dakota | 253 | 2.3
Tennessee | 1,777 | 2.1
Texas | 4,151 | 1.1
Utah | 1,401 | 3.1
Vermont | 139 | 2.7
Virginia | 1,435 | 1.5
Washington | 1,929 | 2.4
West Virginia | 221 | 1.3
Wisconsin | 1,971 | 3.3
Wyoming | 182 | 3.0

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table III Mean age of mother, by live-birth order: United States, 2010–2023, and by race and Hispanic origin of mother: United States, 2016–2023

[Mean age at birth is the arithmetic average of the age of mothers at time of birth, computed directly from the frequency of births by age of mother and live-birth order. Live-birth order refers to number of children born alive to mother]

Race and Hispanic origin and year | Total | Live-birth order
Race and Hispanic origin and year | Total | 1 | 2 | 3 | 4 | 5 | 6 and 7 | 8 and over | Unknown or not stated
All races and origins^1^
2023 | 29.6 | 27.5 | 30.0 | 31.2 | 32.2 | 33.2 | 34.3 | 36.5 | 30.3
2022 | 29.5 | 27.4 | 29.9 | 31.1 | 32.1 | 33.0 | 34.2 | 36.4 | 30.4
2021 | 29.4 | 27.3 | 29.7 | 30.9 | 31.9 | 32.9 | 34.0 | 36.3 | 30.2
2020 | 29.2 | 27.1 | 29.6 | 30.7 | 31.8 | 32.7 | 34.0 | 36.2 | 29.9
2019 | 29.1 | 27.0 | 29.5 | 30.6 | 31.6 | 32.6 | 33.8 | 36.1 | 29.5
2018 | 29.0 | 26.9 | 29.3 | 30.5 | 31.5 | 32.5 | 33.7 | 36.1 | 29.3
2017 | 28.8 | 26.8 | 29.2 | 30.3 | 31.4 | 32.4 | 33.7 | 36.0 | 29.1
2016 | 28.7 | 26.6 | 29.0 | 30.2 | 31.3 | 32.3 | 33.5 | 35.9 | 28.7
2015 | 28.5 | 26.4 | 28.8 | 30.1 | 31.2 | 32.2 | 33.4 | 35.8 | 29.3
2014 | 28.3 | 26.3 | 28.7 | 30.0 | 31.1 | 32.0 | 33.4 | 35.7 | 28.7
2013 | 28.2 | 26.0 | 28.6 | 29.9 | 31.0 | 32.0 | 33.3 | 35.7 | 28.3
2012 | 28.0 | 25.8 | 28.4 | 29.8 | 30.9 | 31.9 | 33.2 | 35.7 | 27.9
2011 | 27.9 | 25.6 | 28.3 | 29.7 | 30.8 | 31.8 | 33.1 | 35.5 | 28.2
2010 | 27.7 | 25.4 | 28.2 | 29.6 | 30.7 | 31.7 | 33.0 | 35.7 | 27.7
Non-Hispanic, single race^2^
American Indian and Alaska Native:
2023 | 27.8 | 24.2 | 27.2 | 29.2 | 31.1 | 32.5 | 33.6 | 35.4 | 28.6
2022 | 27.7 | 24.2 | 27.1 | 29.0 | 30.8 | 32.1 | 33.4 | 35.5 | 27.8
2021 | 27.5 | 23.9 | 26.8 | 28.9 | 30.6 | 31.9 | 33.1 | 35.3 | 27.0
2020 | 27.3 | 23.8 | 26.7 | 28.7 | 30.4 | 31.6 | 32.9 | 35.2 | 27.3
2019 | 27.1 | 23.5 | 26.5 | 28.6 | 30.0 | 31.2 | 32.9 | 34.9 | 27.0
2018 | 27.1 | 23.5 | 26.4 | 28.4 | 30.0 | 31.1 | 32.8 | 34.8 | 27.6
2017 | 26.8 | 23.3 | 26.1 | 28.1 | 29.6 | 31.3 | 32.6 | 34.4 | 27.8
2016 | 26.7 | 23.2 | 26.1 | 28.0 | 29.6 | 31.1 | 32.0 | 34.8 | 28.1
Asian:
2023 | 32.7 | 31.5 | 33.4 | 34.2 | 34.5 | 34.9 | 35.5 | 37.0 | 33.1
2022 | 32.6 | 31.4 | 33.3 | 34.1 | 34.5 | 35.0 | 35.5 | 36.5 | 33.1
2021 | 32.4 | 31.2 | 33.1 | 34.0 | 34.3 | 34.7 | 35.4 | 36.1 | 32.4
2020 | 32.2 | 30.9 | 32.9 | 33.8 | 34.1 | 34.7 | 35.4 | 36.8 | 32.6
2019 | 32.0 | 30.7 | 32.7 | 33.6 | 34.1 | 34.5 | 35.3 | 36.6 | 32.3
2018 | 31.8 | 30.5 | 32.6 | 33.5 | 34.0 | 34.4 | 35.0 | 36.5 | 31.6
2017 | 31.7 | 30.3 | 32.5 | 33.4 | 33.9 | 34.4 | 35.2 | 36.3 | 32.0
2016 | 31.5 | 30.1 | 32.3 | 33.3 | 33.6 | 34.1 | 34.9 | 36.3 | 31.4
Black:
2023 | 28.9 | 25.9 | 29.0 | 30.7 | 31.8 | 32.6 | 33.6 | 35.4 | 30.1
2022 | 28.7 | 25.8 | 28.8 | 30.6 | 31.6 | 32.3 | 33.3 | 35.4 | 30.3
2021 | 28.4 | 25.5 | 28.5 | 30.3 | 31.3 | 32.1 | 33.2 | 35.2 | 29.6
2020 | 28.2 | 25.3 | 28.3 | 30.0 | 31.0 | 31.8 | 32.9 | 35.1 | 29.2
2019 | 28.0 | 25.2 | 28.1 | 29.7 | 30.8 | 31.6 | 32.7 | 35.0 | 28.7
2018 | 27.9 | 25.1 | 28.0 | 29.6 | 30.6 | 31.5 | 32.6 | 34.9 | 28.4
2017 | 27.7 | 24.9 | 27.7 | 29.3 | 30.4 | 31.3 | 32.5 | 34.9 | 28.0
2016 | 27.4 | 24.8 | 27.6 | 29.1 | 30.2 | 31.1 | 32.3 | 34.6 | 27.1
Native Hawaiian and Other Pacific Islander:
2023 | 28.5 | 25.2 | 27.6 | 29.1 | 30.9 | 32.4 | 33.6 | 35.9 | 27.2
2022 | 28.4 | 25.2 | 27.4 | 29.3 | 30.8 | 32.0 | 33.6 | 35.9 | 27.2
2021 | 28.3 | 25.2 | 27.2 | 29.1 | 30.8 | 32.1 | 33.3 | 36.0 | 27.8
2020 | 28.2 | 25.0 | 27.4 | 29.1 | 30.6 | 31.8 | 33.6 | 35.4 | 27.6
2019 | 28.1 | 24.8 | 27.3 | 29.0 | 30.4 | 31.7 | 33.2 | 35.7 | 26.6
2018 | 27.9 | 24.7 | 26.9 | 28.9 | 30.5 | 31.7 | 33.0 | 35.8 | 27.2
2017 | 28.0 | 24.9 | 27.2 | 28.9 | 30.5 | 31.4 | 33.0 | 35.4 | 26.8
2016 | 27.9 | 24.8 | 27.0 | 28.9 | 30.1 | 31.7 | 33.2 | 35.3 | 27.6
White:
2023 | 30.0 | 28.3 | 30.4 | 31.4 | 32.3 | 33.1 | 34.4 | 37.2 | 30.5
2022 | 29.9 | 28.2 | 30.4 | 31.3 | 32.1 | 33.0 | 34.4 | 37.1 | 30.7
2021 | 29.9 | 28.1 | 30.3 | 31.2 | 32.1 | 33.0 | 34.2 | 37.0 | 30.7
2020 | 29.7 | 27.9 | 30.1 | 31.1 | 31.9 | 32.8 | 34.2 | 37.0 | 30.3
2019 | 29.6 | 27.8 | 30.0 | 30.9 | 31.8 | 32.7 | 34.1 | 36.9 | 30.0
2018 | 29.4 | 27.7 | 29.8 | 30.8 | 31.7 | 32.7 | 34.1 | 36.8 | 29.6
2017 | 29.3 | 27.6 | 29.7 | 30.7 | 31.6 | 32.6 | 34.0 | 36.8 | 29.5
2016 | 29.2 | 27.4 | 29.5 | 30.6 | 31.5 | 32.5 | 33.9 | 36.7 | 29.4
Hispanic^3^
2023 | 28.5 | 25.7 | 28.6 | 30.6 | 32.2 | 33.5 | 34.7 | 36.0 | 29.0
2022 | 28.5 | 25.7 | 28.5 | 30.5 | 32.2 | 33.4 | 34.6 | 35.8 | 29.1
2021 | 28.4 | 25.5 | 28.3 | 30.4 | 32.0 | 33.3 | 34.5 | 35.7 | 29.2
2020 | 28.3 | 25.3 | 28.2 | 30.3 | 31.9 | 33.2 | 34.5 | 35.7 | 29.1
2019 | 28.2 | 25.1 | 28.1 | 30.2 | 31.8 | 33.1 | 34.3 | 35.6 | 28.5
2018 | 28.1 | 25.0 | 28.0 | 30.1 | 31.7 | 33.0 | 34.1 | 35.6 | 29.2
2017 | 28.0 | 24.8 | 27.8 | 29.9 | 31.6 | 32.9 | 34.1 | 35.5 | 29.0
2016 | 27.8 | 24.7 | 27.6 | 29.8 | 31.5 | 32.7 | 34.0 | 35.3 | 28.3

1 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

2 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. People of Hispanic origin may be of any race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table IV Births to unmarried women, by race and Hispanic origin of mother: United States, each state and territory, 2023

[By place of residence]

Area | All races and origins^2^ | Non-Hispanic, single race^1^ | | Hispanic^3^ | All races and origins^2^ | Non-Hispanic, single race^1^ | | Hispanic^3^
Area | All races and origins^2^ | Black | White | Hispanic^3^ | All races and origins^2^ | Black | White | Hispanic^3^
| Number | | | | Percent
United States^4^ | 1,440,031 | 340,748 | 479,646 | 511,844 | 40.0 | 69.3 | 26.8 | 54.2
Alabama | 26,598 | 12,344 | 9,752 | 3,608 | 46.0 | 79.4 | 29.3 | 52.4
Alaska | 3,309 | 69 | 870 | 248 | 36.7 | 32.5 | 20.0 | 31.3
Arizona | 35,556 | 2,622 | 8,720 | 19,889 | 45.5 | 60.5 | 29.4 | 56.5
Arkansas | 16,244 | 5,247 | 7,658 | 2,243 | 46.1 | 82.3 | 34.6 | 52.1
California | 154,739 | 11,125 | 21,719 | 103,484 | 38.7 | 60.7 | 20.8 | 53.1
Colorado | 14,793 | 1,270 | 4,951 | 7,292 | 24.1 | 43.7 | 14.7 | 37.3
Connecticut | 12,955 | 2,522 | 3,709 | 6,122 | 37.5 | 62.2 | 20.6 | 62.5
Delaware | 4,889 | 1,863 | 1,504 | 1,235 | 46.9 | 69.2 | 32.0 | 61.3
District of Columbia | 3,668 | 2,599 | 190 | 785 | 46.5 | 77.3 | 7.4 | 55.6
Florida | 101,399 | 30,042 | 29,550 | 38,940 | 45.8 | 66.9 | 32.8 | 51.2
Georgia | 57,981 | 29,365 | 14,100 | 12,102 | 46.3 | 71.4 | 26.8 | 55.0
Hawaii | 6,035 | 48 | 521 | 1,230 | 40.8 | 15.3 | 18.6 | 47.1
Idaho | 5,947 | 93 | 3,502 | 1,996 | 26.6 | 32.0 | 21.0 | 46.8
Illinois | 49,556 | 13,914 | 16,440 | 16,989 | 39.7 | 77.2 | 25.4 | 55.8
Indiana | 33,859 | 7,417 | 18,453 | 6,328 | 42.9 | 73.9 | 34.3 | 59.8
Iowa | 13,039 | 1,591 | 7,969 | 2,418 | 36.2 | 60.9 | 29.6 | 57.4
Kansas | 12,167 | 1,514 | 6,346 | 3,562 | 35.7 | 68.5 | 27.5 | 54.2
Kentucky | 22,144 | 3,326 | 14,890 | 2,957 | 42.6 | 67.4 | 37.5 | 60.9
Louisiana | 30,484 | 16,122 | 9,742 | 3,696 | 55.5 | 82.2 | 35.8 | 62.0
Maine | 4,260 | 257 | 3,652 | 157 | 36.6 | 32.5 | 36.5 | 47.0
Maryland | 26,855 | 11,213 | 5,890 | 8,336 | 40.9 | 59.2 | 22.9 | 57.7
Massachusetts | 22,645 | 3,816 | 8,152 | 9,036 | 33.8 | 52.3 | 22.6 | 57.6
Michigan | 38,311 | 12,972 | 19,039 | 4,099 | 38.6 | 79.5 | 28.1 | 54.3
Minnesota | 19,955 | 3,617 | 8,920 | 3,643 | 32.3 | 48.8 | 22.1 | 56.1
Mississippi | 18,919 | 11,449 | 5,666 | 1,289 | 54.9 | 82.4 | 32.6 | 60.7
Missouri | 26,284 | 6,483 | 14,984 | 2,988 | 39.2 | 76.2 | 30.9 | 54.2
Montana | 3,426 | 15 | 2,197 | 294 | 30.9 | 25.0 | 24.7 | 41.8
Nebraska | 8,325 | 938 | 3,683 | 2,856 | 34.5 | 62.3 | 23.5 | 57.0
Nevada | 15,508 | 2,914 | 3,552 | 7,111 | 48.8 | 71.2 | 34.0 | 56.3
New Hampshire | 3,417 | 120 | 2,749 | 419 | 28.6 | 39.5 | 27.2 | 47.1
New Jersey | 33,855 | 7,610 | 6,897 | 17,751 | 33.5 | 63.3 | 14.9 | 58.7
New Mexico | 11,042 | 199 | 1,673 | 7,285 | 52.7 | 52.2 | 32.0 | 58.5
New York | 76,877 | 17,347 | 23,027 | 31,621 | 37.8 | 66.2 | 22.7 | 62.2
North Carolina | 48,924 | 17,860 | 14,869 | 12,757 | 40.7 | 71.1 | 24.3 | 53.6
North Dakota | 3,085 | 254 | 1,690 | 362 | 32.0 | 46.2 | 24.3 | 47.7
Ohio | 53,790 | 14,734 | 29,601 | 6,045 | 42.4 | 73.3 | 33.3 | 62.0
Oklahoma | 21,456 | 2,647 | 9,123 | 4,728 | 44.8 | 71.9 | 35.8 | 53.7
Oregon | 14,404 | 506 | 7,091 | 4,811 | 37.6 | 50.4 | 31.3 | 54.2
Pennsylvania | 49,205 | 11,677 | 22,665 | 11,693 | 38.8 | 74.1 | 27.5 | 63.2
Rhode Island | 4,261 | 464 | 1,613 | 1,860 | 43.5 | 58.2 | 30.6 | 61.8
South Carolina | 25,908 | 11,419 | 8,753 | 4,405 | 44.9 | 77.4 | 27.5 | 55.4
South Dakota | 3,930 | 132 | 1,834 | 473 | 35.1 | 38.3 | 22.9 | 56.6
Tennessee | 35,261 | 11,113 | 16,096 | 6,734 | 42.5 | 77.3 | 30.4 | 56.6
Texas | 163,261 | 29,776 | 29,522 | 99,063 | 42.1 | 63.2 | 24.8 | 51.6
Utah | 9,581 | 234 | 4,377 | 4,016 | 21.3 | 35.8 | 13.8 | 43.5
Vermont | 1,807 | 46 | 1,627 | 66 | 35.7 | 37.4 | 35.9 | 43.4
Virginia | 32,785 | 11,256 | 11,328 | 8,619 | 35.4 | 63.9 | 23.0 | 53.1
Washington | 25,723 | 1,521 | 10,441 | 8,851 | 31.8 | 41.6 | 24.7 | 51.6
West Virginia | 7,482 | 424 | 6,476 | 249 | 45.1 | 74.0 | 43.6 | 49.2
Wisconsin | 22,157 | 4,629 | 10,604 | 4,681 | 37.1 | 82.8 | 25.6 | 61.7
Wyoming | 1,970 | 13 | 1,269 | 422 | 32.9 | * | 27.9 | 49.2
Puerto Rico | 13,136 | 38 | 204 | 12,879 | 70.6 | 73.1 | 56.0 | 71.0
U.S. Virgin Islands | 581 | 418 | 30 | 124 | 70.6 | 76.1 | 34.1 | 74.7
Guam | 1,461 | * | 24 | * | 62.1 | * | 20.9 | *
American Samoa | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 352 | * | * | * | 60.8 | * | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

--- Data not available.

1 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

4 Excludes data for the territories.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table V Educational attainment of mother, by age and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin of mother and educational attainment | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54
All races and origins^1^ | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
12th grade or less with no diploma | 11.3 | 48.3 | 16.4 | 9.3 | 7.0 | 8.2 | 11.7
8th grade or less | 3.3 | 7.0 | 3.9 | 2.9 | 2.5 | 3.5 | 5.9
9th–12th grade with no diploma | 7.9 | 41.3 | 12.5 | 6.4 | 4.5 | 4.6 | 5.8
High school graduate^2^ | 27.0 | 44.2 | 49.3 | 29.5 | 18.0 | 15.0 | 15.4
Some college credit but no degree | 17.3 | 7.0 | 21.4 | 20.5 | 15.9 | 13.7 | 13.4
Associate’s degree^3^ | 8.3 | 0.6 | 5.9 | 10.1 | 9.1 | 8.3 | 8.0
Bachelor’s degree^4^ | 22.4 | * | 6.3 | 22.5 | 29.8 | 29.3 | 26.3
Master’s degree^5^ | 10.6 | * | 0.6 | 6.8 | 15.7 | 18.7 | 17.9
Doctorate or professional degree^6^ | 3.2 | * | 0.0 | 1.3 | 4.5 | 6.9 | 7.3
| Number
All births | 3,596,017 | 142,743 | 616,970 | 986,567 | 1,098,052 | 604,631 | 147,054
Not stated^7^ | 64,454 | 2,617 | 9,038 | 15,421 | 19,418 | 13,201 | 4,759
Non-Hispanic, single race^8^ | Percent
Black:
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
12th grade or less with no diploma | 11.4 | 44.8 | 11.6 | 8.5 | 8.2 | 9.1 | 10.6
8th grade or less | 1.7 | 2.9 | 0.7 | 1.2 | 1.7 | 2.6 | 4.0
9th–12th grade with no diploma | 9.8 | 42.0 | 10.9 | 7.4 | 6.6 | 6.5 | 6.6
High school graduate^2^ | 38.3 | 47.7 | 57.7 | 40.3 | 29.9 | 23.9 | 21.1
Some college credit but no degree | 21.8 | 7.0 | 22.2 | 24.9 | 23.4 | 20.0 | 17.5
Associate’s degree^3^ | 8.1 | 0.4 | 4.1 | 8.4 | 10.4 | 10.9 | 10.6
Bachelor’s degree^4^ | 13.0 | * | 4.1 | 13.4 | 17.5 | 19.6 | 19.9
Master’s degree^5^ | 6.1 | * | 0.3 | 3.9 | 8.7 | 12.8 | 15.6
Doctorate or professional degree^6^ | 1.4 | * | * | 0.5 | 1.9 | 3.6 | 4.5
| Number
All births | 491,494 | 28,900 | 103,077 | 131,705 | 131,500 | 74,492 | 21,820
Not stated^7^ | 5,343 | 234 | 827 | 1,302 | 1,574 | 1,045 | 361
White: | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
12th grade or less with no diploma | 6.2 | 42.3 | 13.2 | 5.4 | 3.1 | 2.9 | 4.2
8th grade or less | 1.6 | 3.6 | 2.8 | 1.6 | 1.0 | 1.1 | 2.0
9th–12th grade with no diploma | 4.7 | 38.7 | 10.5 | 3.8 | 2.0 | 1.8 | 2.2
High school graduate^2^ | 21.3 | 48.3 | 46.5 | 23.9 | 12.9 | 10.5 | 11.0
Some college credit but no degree | 16.3 | 8.6 | 22.8 | 19.3 | 14.0 | 12.4 | 13.0
Associate’s degree^3^ | 9.3 | 0.7 | 7.6 | 11.4 | 9.4 | 8.3 | 8.3
Bachelor’s degree^4^ | 28.9 | * | 8.9 | 29.1 | 36.2 | 35.1 | 31.6
Master’s degree^5^ | 13.9 | * | 0.9 | 9.2 | 19.0 | 22.7 | 22.7
Doctorate or professional degree^6^ | 4.1 | * | 0.0 | 1.8 | 5.4 | 8.0 | 9.1
| Number
All births | 1,787,051 | 45,273 | 263,760 | 500,910 | 595,741 | 314,198 | 67,169
Not stated^7^ | 13,347 | 389 | 1,666 | 3,180 | 4,223 | 2,899 | 990
Hispanic^9^ | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
12th grade or less with no diploma | 22.1 | 54.3 | 23.1 | 17.4 | 17.2 | 22.5 | 29.7
8th grade or less | 8.3 | 12.3 | 7.3 | 6.7 | 7.2 | 10.9 | 16.4
9th–12th grade with no diploma | 13.8 | 42.0 | 15.7 | 10.8 | 10.0 | 11.5 | 13.3
High school graduate^2^ | 34.8 | 39.5 | 49.1 | 36.1 | 27.5 | 24.1 | 23.1
Some college credit but no degree | 18.0 | 5.6 | 18.8 | 21.2 | 18.8 | 15.5 | 13.3
Associate’s degree^3^ | 7.2 | 0.6 | 4.7 | 8.7 | 9.1 | 7.9 | 6.7
Bachelor’s degree^4^ | 12.6 | * | 3.9 | 13.3 | 18.7 | 18.5 | 16.2
Master’s degree^5^ | 4.1 | * | 0.2 | 2.7 | 7.0 | 8.8 | 8.3
Doctorate or professional degree^6^ | 1.1 | * | 0.0 | 0.5 | 1.7 | 2.7 | 2.8
| Number
All births | 945,200 | 58,714 | 207,702 | 270,317 | 240,489 | 131,623 | 36,355
Not stated^7^ | 21,465 | 1,446 | 4,219 | 5,802 | 5,450 | 3,391 | 1,157

* Estimate does not meet National Center for Health Statistics standards of reliability.

0.0 Quantity more than zero but less than 0.05.

1 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

2 Includes GED.

3 Includes associate in arts and associate in science.

4 Includes bachelor in arts and bachelor in science.

5 Includes master in arts, master in science, master in engineering, master in education, master in social work, and master in business administration.

6 Includes doctor of philosophy, doctor of education, doctor of medicine, doctor of dental surgery, doctor of veterinary medicine, doctor of laws, and juris doctor.

7 No response reported for education attainment of mother item; see Technical Notes in this report.

8 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

9 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table VI Maternal prepregnancy body mass index, by age and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin of mother and BMI category^1^ | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54
All races and origins^2^ | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
Underweight (BMI less than 18.5) | 2.7 | 8.1 | 4.6 | 2.4 | 1.9 | 1.6 | 1.4
Normal weight (BMI 18.5–24.9) | 37.6 | 49.1 | 38.4 | 35.3 | 38.0 | 37.7 | 34.9
Overweight (BMI 25.0–29.9) | 27.7 | 23.3 | 25.9 | 27.8 | 28.3 | 28.9 | 30.2
Obese (BMI 30.0 and over) | 32.0 | 19.5 | 31.2 | 34.5 | 31.8 | 31.8 | 33.5
| Number
Total | 3,596,017 | 142,743 | 616,970 | 986,567 | 1,098,052 | 604,631 | 147,054
Not stated^3^ | 82,194 | 4,513 | 14,508 | 21,312 | 23,521 | 14,247 | 4,093
Non-Hispanic, single race^4^
Black: | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
Underweight (BMI less than 18.5) | 2.7 | 7.0 | 4.7 | 2.6 | 1.5 | 1.1 | 0.8
Normal weight (BMI 18.5–24.9) | 28.5 | 48.6 | 36.7 | 28.2 | 23.5 | 21.0 | 19.5
Overweight (BMI 25.0–29.9) | 26.7 | 22.7 | 24.1 | 26.2 | 27.9 | 29.5 | 30.3
Obese (BMI 30.0 and over) | 42.2 | 21.7 | 34.5 | 43.0 | 47.0 | 48.5 | 49.4
| Number
Total | 491,494 | 28,900 | 103,077 | 131,705 | 131,500 | 74,492 | 21,820
Not stated^3^ | 13,388 | 833 | 2,489 | 3,487 | 3,636 | 2,223 | 720
White: | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
Underweight (BMI less than 18.5) | 2.7 | 10.9 | 5.3 | 2.5 | 1.8 | 1.7 | 1.5
Normal weight (BMI 18.5–24.9) | 41.6 | 49.0 | 40.7 | 39.2 | 42.9 | 42.8 | 41.1
Overweight (BMI 25.0–29.9) | 26.4 | 20.7 | 23.9 | 26.6 | 27.2 | 27.2 | 28.0
Obese (BMI 30.0 and over) | 29.3 | 19.4 | 30.1 | 31.8 | 28.1 | 28.3 | 29.4
| Number
Total | 1,787,051 | 45,273 | 263,760 | 500,910 | 595,741 | 314,198 | 67,169
Not stated^3^ | 27,701 | 766 | 3,927 | 6,925 | 9,001 | 5,569 | 1,513
Hispanic^5^ | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
Underweight (BMI less than 18.5) | 2.1 | 6.5 | 3.5 | 1.7 | 1.1 | 0.9 | 0.7
Normal weight (BMI 18.5–24.9) | 31.1 | 49.5 | 36.0 | 29.2 | 28.0 | 27.0 | 24.7
Overweight (BMI 25.0–29.9) | 31.2 | 25.7 | 29.3 | 31.3 | 32.3 | 33.3 | 35.1
Obese (BMI 30.0 and over) | 35.6 | 18.3 | 31.3 | 37.8 | 38.7 | 38.9 | 39.5
| Number
Total | 945,200 | 58,714 | 207,702 | 270,317 | 240,489 | 131,623 | 36,355
Not stated^3^ | 29,176 | 2,527 | 6,582 | 8,056 | 6,902 | 3,969 | 1,140

1 For calculation of body mass index (BMI), see Technical Notes in this report.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 No response reported for component measures for prepregnancy BMI; see Technical Notes.

4 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

5 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table VII Mother received WIC food for herself during this pregnancy and infant was being breastfed at discharge, by age and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin of mother and selected characteristic | All births | Characteristic reported | Age of mother | | | | | | | Not stated^1^
Race and Hispanic origin of mother and selected characteristic | All births | Characteristic reported | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54 | Not stated^1^
All races and origins^2^ | Number | | Percent | | | | | | | Number
Mother received WIC food for herself during this pregnancy | 3,596,017 | 1,124,928 | 31.6 | 63.1 | 50.4 | 32.8 | 22.8 | 21.3 | 23.6 | 40,083
Infant was being breastfed at discharge^3^ | 3,195,909 | 2,689,383 | 84.8 | 74.1 | 80.4 | 85.1 | 87.1 | 87.3 | 86.3 | 24,703
Non-Hispanic, single race^4^
Black:
Mother received WIC food for herself during this pregnancy | 491,494 | 225,886 | 46.5 | 63.3 | 56.5 | 47.1 | 41.3 | 37.6 | 34.7 | 5,495
Infant was being breastfed at discharge^3^ | 473,154 | 356,589 | 75.9 | 62.6 | 70.6 | 76.3 | 79.1 | 80.8 | 82.1 | 3,619
White:
Mother received WIC food for herself during this pregnancy | 1,787,051 | 346,075 | 19.5 | 60.4 | 40.7 | 20.4 | 11.9 | 10.7 | 11.9 | 15,636
Infant was being breastfed at discharge^3^ | 1,682,670 | 1,436,446 | 86.0 | 72.7 | 80.8 | 86.2 | 88.1 | 88.3 | 87.1 | 13,004
Hispanic^5^
Mother received WIC food for herself during this pregnancy | 945,200 | 464,812 | 49.7 | 65.5 | 60.0 | 49.4 | 42.4 | 41.8 | 43.8 | 9,075
Infant was being breastfed at discharge^3^ | 750,261 | 649,282 | 87.1 | 82.2 | 85.6 | 87.7 | 88.5 | 88.2 | 87.2 | 4,698

1 No response reported for selected characteristic.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, as well as non-Hispanic multiple-race women, and births with origin not stated.

3 Excludes data for California, which did not report if infant was being breastfed at discharge.

4 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

5 Includes all people of Hispanic origin of any race; see Technical Notes.

NOTE: WIC is Special Supplemental Nutrition Program for Women, Infants, and Children.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table VIII Pregnancy risk factors, by age and race and Hispanic origin of mother: United States, 2023

[Rates are number of live births with specified risk factor per 1,000 live births in specified group]

Race and Hispanic origin of mother and risk factor | All births | Factor reported | Age of mother | | | | | | | Not stated^1^
Race and Hispanic origin of mother and risk factor | All births | Factor reported | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54 | Not stated^1^
All races and origins^2^ | Number | | Rate per 1,000 | | | | | | | Number
Diabetes:
Prepregnancy (diagnosis before this pregnancy) | 3,596,017 | 44,601 | 12.4 | 4.3 | 7.4 | 10.3 | 12.9 | 18.4 | 27.4 | 5,752
Gestational (diagnosis during thispregnancy) | 3,596,017 | 296,661 | 82.6 | 24.7 | 46.3 | 71.1 | 91.9 | 119.1 | 149.7 | 5,752
Hypertension:
Prepregnancy (chronic) | 3,596,017 | 113,272 | 31.5 | 9.9 | 19.5 | 26.7 | 32.9 | 46.0 | 66.4 | 5,752
Gestational (PIH^3^, preeclampsia) | 3,596,017 | 361,780 | 100.8 | 101.0 | 100.6 | 101.1 | 97.5 | 101.9 | 118.6 | 5,752
Eclampsia | 3,596,017 | 8,494 | 2.4 | 3.2 | 2.6 | 2.3 | 2.1 | 2.3 | 3.0 | 5,752
Previous preterm birth | 3,596,017 | 142,384 | 39.7 | 8.0 | 26.0 | 37.6 | 43.5 | 52.3 | 60.1 | 5,752
Pregnancy resulted from infertility treatment | 3,596,017 | 88,185 | 24.6 | 0.2 | 2.3 | 9.7 | 25.5 | 52.5 | 120.0 | 5,752
Mother had a previous cesarean delivery^4^ | 2,431,984 | 549,988 | 226.4 | 95.2 | 156.1 | 202.5 | 237.0 | 275.0 | 297.7 | 3,075
Non-Hispanic, single race^5^
Black:
Diabetes:
Prepregnancy (diagnosis before this pregnancy) | 491,494 | 8,285 | 16.9 | 5.4 | 8.7 | 13.3 | 19.1 | 27.8 | 41.7 | 869
Gestational (diagnosis during this pregnancy) | 491,494 | 32,780 | 66.8 | 18.1 | 34.4 | 56.0 | 80.9 | 106.4 | 129.4 | 869
Hypertension:
Prepregnancy (chronic) | 491,494 | 28,331 | 57.7 | 15.3 | 30.3 | 46.9 | 67.0 | 94.6 | 127.2 | 869
Gestational (PIH^3^, preeclampsia) | 491,494 | 57,704 | 117.6 | 126.4 | 118.0 | 113.2 | 114.7 | 120.5 | 138.6 | 869
Eclampsia | 491,494 | 1,553 | 3.2 | 4.3 | 3.2 | 2.9 | 3.0 | 3.4 | 3.4 | 869
Previous preterm birth | 491,494 | 30,597 | 62.4 | 9.7 | 36.4 | 63.4 | 77.6 | 83.2 | 85.8 | 869
Pregnancy resulted from infertility treatment | 491,494 | 5,237 | 10.7 | * | 1.1 | 3.7 | 10.0 | 23.0 | 73.6 | 869
Mother had a previous cesarean delivery^4^ | 354,349 | 88,906 | 251.3 | 96.0 | 167.0 | 231.5 | 274.8 | 310.1 | 317.9 | 576
White:
Diabetes:
Prepregnancy (diagnosis before this pregnancy) | 1,787,051 | 17,504 | 9.8 | 4.7 | 7.5 | 8.9 | 9.7 | 12.4 | 17.4 | 2,388
Gestational (diagnosis during this pregnancy) | 1,787,051 | 133,748 | 74.9 | 29.2 | 48.7 | 67.5 | 78.6 | 98.0 | 123.7 | 2,388
Hypertension:
Prepregnancy (chronic) | 1,787,051 | 55,576 | 31.1 | 11.2 | 21.9 | 27.5 | 31.4 | 41.6 | 57.3 | 2,388
Gestational (PIH^3^, preeclampsia) | 1,787,051 | 194,706 | 109.1 | 111.1 | 112.2 | 113.7 | 104.5 | 105.4 | 119.3 | 2,388
Eclampsia | 1,787,051 | 4,190 | 2.3 | 3.9 | 2.7 | 2.4 | 2.0 | 2.2 | 2.9 | 2,388
Previous preterm birth | 1,787,051 | 64,228 | 36.0 | 8.0 | 24.4 | 32.7 | 37.8 | 47.3 | 55.4 | 2,388
Pregnancy resulted from infertility treatment | 1,787,051 | 58,982 | 33.0 | * | 3.7 | 14.2 | 33.3 | 66.5 | 152.3 | 2,388
Mother had a previous cesarean delivery^4^ | 1,194,321 | 252,419 | 211.6 | 83.1 | 143.9 | 184.0 | 218.6 | 257.5 | 285.2 | 1,437
Hispanic^6^ | Number | | Rate per 1,000 | | | | | | | Number
Diabetes:
Prepregnancy (diagnosis before this pregnancy) | 945,200 | 13,060 | 13.8 | 3.2 | 6.5 | 10.8 | 16.5 | 25.3 | 36.3 | 1,245
Gestational (diagnosis during thispregnancy) | 945,200 | 82,280 | 87.2 | 23.5 | 46.3 | 75.4 | 105.4 | 144.7 | 182.1 | 1,245
Hypertension:
Prepregnancy (chronic) | 945,200 | 19,606 | 20.8 | 6.1 | 11.1 | 16.9 | 23.6 | 36.1 | 54.3 | 1,245
Gestational (PIH^3^, preeclampsia) | 945,200 | 77,867 | 82.5 | 79.7 | 78.3 | 77.5 | 82.6 | 92.6 | 110.8 | 1,245
Eclampsia | 945,200 | 1,839 | 1.9 | 2.2 | 2.0 | 1.9 | 1.8 | 2.0 | 2.9 | 1,245
Previous preterm birth | 945,200 | 34,496 | 36.5 | 7.0 | 22.4 | 35.1 | 44.4 | 53.7 | 61.6 | 1,245
Pregnancy resulted from infertility treatment | 945,200 | 9,222 | 9.8 | 0.3 | 1.0 | 4.1 | 11.4 | 23.4 | 57.0 | 1,245
Mother had a previous cesarean delivery^4^ | 645,518 | 154,369 | 239.4 | 107.2 | 166.3 | 220.4 | 261.9 | 295.9 | 306.6 | 735

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 No response reported for pregnancy risk factor item.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 PIH is pregnancy-induced hypertension.

4 Excludes women who have not had a previous pregnancy and for whom total birth order is unknown.

5 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

6 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table IX Infections present or treated during this pregnancy, by age and race and Hispanic origin of mother: United States, 2023

[Rates are number of live births with specified infection per 100,000 live births in specified group]

Race and Hispanic origin of mother and infection | All births | Infection present | Age of mother | | | | | | | Not stated^1^
Race and Hispanic origin of mother and infection | All births | Infection present | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54 | Not stated^1^
All races and origins^2^ | Number | | Rate per 100,000 | | | | | | | Number
Gonorrhea | 3,596,017 | 9,406 | 262.8 | 1,198.5 | 543.5 | 228.4 | 133.2 | 96.2 | 63.6 | 17,548
Syphilis | 3,596,017 | 11,615 | 324.6 | 473.8 | 469.5 | 346.6 | 262.7 | 241.0 | 230.4 | 17,548
Chlamydia | 3,596,017 | 62,428 | 1,744.5 | 7,826.1 | 4,021.5 | 1,543.0 | 738.3 | 478.6 | 372.6 | 17,548
Hepatitis B | 3,596,017 | 6,019 | 168.2 | 54.3 | 83.4 | 124.4 | 178.4 | 276.4 | 407.5 | 17,548
Hepatitis C | 3,596,017 | 14,215 | 397.2 | 117.0 | 192.1 | 383.9 | 500.9 | 495.4 | 441.0 | 17,548
Non-Hispanic, single race^3^
Black:
Gonorrhea | 491,494 | 4,500 | 921.3 | 3,520.8 | 1,688.4 | 734.4 | 433.8 | 271.5 | 138.4 | 3,062
Syphilis | 491,494 | 3,842 | 786.6 | 877.6 | 1,030.6 | 832.2 | 671.8 | 628.2 | 470.7 | 3,062
Chlamydia | 491,494 | 19,572 | 4,007.1 | 14,452.4 | 7,441.8 | 3,431.8 | 1,812.6 | 1,080.7 | 632.2 | 3,062
Hepatitis B | 491,494 | 1,801 | 368.7 | 52.2 | 140.5 | 283.5 | 431.5 | 703.8 | 858.3 | 3,062
Hepatitis C | 491,494 | 916 | 187.5 | 118.4 | 133.7 | 188.0 | 198.2 | 245.9 | 267.7 | 3,062
White:
Gonorrhea | 1,787,051 | 2,294 | 128.9 | 532.8 | 279.8 | 121.9 | 79.7 | 64.9 | 52.4 | 7,649
Syphilis | 1,787,051 | 3,103 | 174.4 | 262.0 | 246.3 | 184.6 | 148.2 | 139.7 | 151.1 | 7,649
Chlamydia | 1,787,051 | 16,276 | 914.7 | 5,003.9 | 2,468.3 | 841.2 | 394.8 | 271.4 | 227.5 | 7,649
Hepatitis B | 1,787,051 | 1,114 | 62.6 | 44.4 | 48.4 | 51.9 | 62.5 | 80.2 | 128.7 | 7,649
Hepatitis C | 1,787,051 | 10,583 | 594.8 | 131.0 | 286.3 | 564.3 | 717.4 | 721.5 | 664.4 | 7,649
Hispanic^4^
Gonorrhea | 945,200 | 1,754 | 186.5 | 507.8 | 280.3 | 174.7 | 116.1 | 84.7 | 55.3 | 4,709
Syphilis | 945,200 | 3,374 | 358.7 | 394.6 | 439.5 | 376.5 | 321.7 | 265.6 | 290.2 | 4,709
Chlamydia | 945,200 | 21,416 | 2,277.1 | 6,506.8 | 4,200.4 | 1,940.8 | 1,088.4 | 704.5 | 539.0 | 4,709
Hepatitis B | 945,200 | 756 | 80.4 | 58.3 | 66.8 | 75.1 | 81.5 | 108.4 | 124.4 | 4,709
Hepatitis C | 945,200 | 1,425 | 151.5 | 97.8 | 88.6 | 138.3 | 192.2 | 209.9 | 215.6 | 4,709

1 No response reported for infections present or treated during this pregnancy item.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table X External cephalic version, by age and race and Hispanic origin of mother: United States, 2023

[Rates are number of live births with specified obstetric procedure per 1,000 live births in specified group]

Race and Hispanic origin of mother | All births^1^ | Procedure reported | Age of mother | | | | | | | Not stated^2^
Race and Hispanic origin of mother | All births^1^ | Procedure reported | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54 | Not stated^2^
All races and origins^3^ | Number | | Rate per 1,000 | | | | | | | Number
External cephalic version | 3,596,017 | 11,814 | 3.3 | 2.1 | 2.3 | 3.0 | 3.6 | 4.1 | 4.3 | 6,995
Percent successful^4^ | 11,814 | 5,776 | 48.9 | 46.6 | 46.4 | 46.8 | 47.6 | 52.0 | 61.0 | –
Non-Hispanic, single race^5^
Black:
External cephalic version | 491,494 | 972 | 2.0 | 1.5 | 1.5 | 1.8 | 2.1 | 2.6 | 2.9 | 1,116
Percent successful^4^ | 972 | 592 | 60.9 | 79.5 | 68.6 | 59.6 | 56.9 | 57.7 | 60.9 | –
White:
External cephalic version | 1,787,051 | 7,642 | 4.3 | 2.7 | 3.0 | 3.9 | 4.6 | 5.1 | 5.7 | 2,459
Percent successful^4^ | 7,642 | 3,704 | 48.5 | 38.5 | 46.2 | 45.9 | 47.3 | 51.8 | 63.9 | –
Hispanic^6^
External cephalic version | 945,200 | 2,060 | 2.2 | 1.9 | 1.7 | 2.0 | 2.4 | 2.7 | 3.1 | 2,008
Percent successful^4^ | 2,060 | 984 | 47.8 | 44.0 | 38.9 | 48.8 | 46.2 | 55.3 | 58.4 | –

– Quantity zero.

1 Number for percent successful is women with an external cephalic version (ECV) in specified group.

2 No response reported for obstetric procedure item.

3 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

4 Percent successful ECV is the number of successful ECVs per 100 live births to women with an ECV in specified group.

5 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

6 Includes all people of Hispanic origin of any race; see Technical Notes.

NOTE: External cephalic version is attempted conversion of a fetus from a nonvertex to a vertex (head first) presentation by external manipulation.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XI Characteristics of labor and delivery, by age and race and Hispanic origin of mother: United States, 2023

[Rates are number of live births with characteristic per 1,000 live births in specified group]

Race and Hispanic origin of mother and labor and delivery characteristic | All births | Characteristic reported | Age of mother | | | | | | | Not stated^1^
Race and Hispanic origin of mother and labor and delivery characteristic | All births | Characteristic reported | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54 | Not stated^1^
All races and origins^2^ | Number | | Rate per 1,000 | | | | | | | Number
Induction of labor | 3,596,017 | 1,191,790 | 331.6 | 370.3 | 359.6 | 340.1 | 317.0 | 307.8 | 326.0 | 2,050
Augmentation of labor | 3,596,017 | 750,824 | 208.9 | 262.6 | 238.9 | 219.6 | 203.3 | 174.2 | 143.9 | 2,050
Steroids (glucocorticoids) for fetal lung maturation | 3,596,017 | 138,415 | 38.5 | 42.5 | 38.0 | 36.7 | 37.0 | 40.8 | 51.1 | 2,050
Antibiotics received by mother during labor | 3,596,017 | 899,530 | 250.3 | 261.1 | 250.5 | 243.3 | 247.2 | 258.3 | 275.7 | 2,050
Clinical chorioamnionitis during labor | 3,596,017 | 63,491 | 17.7 | 25.2 | 21.2 | 18.0 | 16.8 | 14.4 | 13.2 | 2,050
Epidural or spinal anesthesia during labor | 3,596,017 | 2,803,292 | 780.0 | 816.7 | 793.6 | 779.6 | 777.1 | 767.8 | 761.5 | 2,050
Non-Hispanic, single race^3^
Black:
Induction of labor | 491,494 | 154,278 | 314.0 | 378.6 | 349.6 | 311.3 | 289.9 | 289.0 | 307.1 | 169
Augmentation of labor | 491,494 | 90,411 | 184.0 | 233.8 | 215.5 | 191.9 | 171.4 | 148.0 | 120.6 | 169
Steroids (glucocorticoids) for fetal lung maturation | 491,494 | 26,108 | 53.1 | 51.8 | 48.5 | 50.7 | 54.0 | 58.2 | 68.6 | 169
Antibiotics received by mother during labor | 491,494 | 137,195 | 279.2 | 317.7 | 295.7 | 276.3 | 267.8 | 266.6 | 280.4 | 169
Clinical chorioamnionitis during labor | 491,494 | 7,772 | 15.8 | 21.1 | 19.8 | 16.7 | 14.0 | 11.5 | 10.1 | 169
Epidural or spinal anesthesia during labor | 491,494 | 379,782 | 773.0 | 821.6 | 797.8 | 770.2 | 756.0 | 757.1 | 764.6 | 169
White:
Induction of labor | 1,787,051 | 646,185 | 361.8 | 435.9 | 403.0 | 376.2 | 344.1 | 329.9 | 347.7 | 890
Augmentation of labor | 1,787,051 | 370,988 | 207.7 | 250.3 | 231.8 | 220.2 | 206.6 | 176.9 | 144.7 | 890
Steroids (glucocorticoids) for fetal lung maturation | 1,787,051 | 67,580 | 37.8 | 46.3 | 39.9 | 36.9 | 35.6 | 38.6 | 47.2 | 890
Antibiotics received by mother during labor | 1,787,051 | 427,721 | 239.5 | 247.6 | 235.7 | 232.9 | 237.9 | 249.4 | 265.4 | 890
Clinical chorioamnionitis during labor | 1,787,051 | 22,381 | 12.5 | 14.5 | 12.9 | 12.7 | 12.9 | 11.4 | 10.3 | 890
Epidural or spinal anesthesia during labor | 1,787,051 | 1,402,835 | 785.4 | 839.5 | 802.1 | 787.8 | 783.7 | 768.7 | 758.4 | 890
Hispanic^4^
Induction of labor | 945,200 | 274,305 | 290.3 | 313.3 | 312.2 | 292.6 | 271.1 | 272.3 | 304.2 | 455
Augmentation of labor | 945,200 | 204,082 | 216.0 | 284.8 | 256.1 | 222.5 | 194.6 | 167.5 | 145.0 | 455
Steroids (glucocorticoids) for fetal lung maturation | 945,200 | 31,328 | 33.2 | 34.1 | 30.3 | 30.3 | 33.3 | 38.6 | 48.6 | 455
Antibiotics received by mother during labor | 945,200 | 234,261 | 248.0 | 240.0 | 242.8 | 241.6 | 250.3 | 261.4 | 273.4 | 455
Clinical chorioamnionitis during labor | 945,200 | 22,142 | 23.4 | 35.9 | 31.9 | 24.6 | 18.3 | 14.3 | 13.1 | 455
Epidural or spinal anesthesia during labor | 945,200 | 728,861 | 771.5 | 800.9 | 786.5 | 771.2 | 762.7 | 756.8 | 751.8 | 455

1 No response reported for selected characteristic.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XII Total cesarean delivery and low-risk cesarean delivery, by race and Hispanic origin of mother: United States, each state and territory, 2023

[By place of residence]

Area | Total cesarean delivery rate^1^ | | | | Low-risk cesarean delivery rate^2^
Area | All races and origins^4^ | Non-Hispanic, single race^3^ | | Hispanic^5^ | All races and origins^4^ | Non-Hispanic, single race^3^ | | Hispanic^5^
Area | All races and origins^4^ | Black | White | Hispanic^5^ | All races and origins^4^ | Black | White | Hispanic^5^
United States^6^ | 32.3 | 37.0 | 31.1 | 32.0 | 26.6 | 30.8 | 25.6 | 25.9
Alabama | 34.2 | 37.9 | 33.9 | 26.7 | 28.3 | 31.6 | 27.9 | 21.9
Alaska | 24.0 | 38.7 | 25.7 | 28.2 | 20.5 | 25.7 | 22.3 | 20.9
Arizona | 29.0 | 34.5 | 28.1 | 28.9 | 23.4 | 30.5 | 22.2 | 23.3
Arkansas | 33.8 | 39.2 | 32.9 | 30.3 | 26.9 | 32.7 | 25.8 | 24.5
California | 31.5 | 36.8 | 30.9 | 31.1 | 25.9 | 31.2 | 25.5 | 25.0
Colorado | 27.5 | 32.8 | 27.2 | 26.6 | 23.1 | 26.2 | 22.6 | 22.6
Connecticut | 35.0 | 39.3 | 34.6 | 33.5 | 30.0 | 34.9 | 30.0 | 27.1
Delaware | 31.5 | 34.7 | 30.2 | 30.0 | 24.2 | 27.5 | 23.2 | 20.9
District of Columbia | 34.1 | 35.1 | 34.0 | 30.4 | 29.7 | 29.6 | 29.6 | 28.1
Florida | 36.2 | 38.1 | 33.4 | 38.7 | 29.9 | 31.0 | 27.2 | 32.5
Georgia | 35.8 | 38.2 | 35.4 | 31.9 | 29.8 | 32.4 | 29.1 | 25.4
Hawaii | 27.4 | 31.9 | 25.4 | 26.8 | 23.7 | 30.3 | 20.3 | 23.1
Idaho | 24.4 | 27.5 | 23.7 | 26.5 | 19.8 | 24.3 | 19.0 | 22.1
Illinois | 31.0 | 33.7 | 30.8 | 29.9 | 24.2 | 25.7 | 23.8 | 23.8
Indiana | 30.7 | 34.4 | 30.5 | 28.9 | 25.0 | 27.0 | 25.1 | 22.5
Iowa | 30.2 | 35.0 | 29.7 | 29.8 | 24.5 | 31.2 | 24.0 | 24.4
Kansas | 30.3 | 36.2 | 30.2 | 27.8 | 24.8 | 30.3 | 24.7 | 22.6
Kentucky | 34.3 | 35.9 | 34.2 | 33.0 | 27.2 | 30.2 | 27.1 | 25.6
Louisiana | 36.1 | 38.1 | 35.7 | 31.6 | 28.3 | 29.7 | 28.3 | 24.6
Maine | 31.1 | 32.4 | 30.9 | 30.5 | 25.5 | 29.7 | 25.1 | 23.3
Maryland | 35.0 | 41.1 | 33.0 | 30.2 | 30.3 | 35.6 | 29.2 | 24.4
Massachusetts | 33.5 | 38.2 | 32.7 | 33.8 | 27.5 | 34.8 | 26.9 | 25.7
Michigan | 33.2 | 36.1 | 32.3 | 32.0 | 28.4 | 30.3 | 27.5 | 27.1
Minnesota | 30.2 | 34.8 | 29.8 | 29.6 | 26.6 | 34.3 | 25.6 | 26.4
Mississippi | 37.9 | 40.4 | 36.8 | 29.7 | 30.1 | 32.2 | 28.9 | 23.2
Missouri | 30.2 | 32.4 | 29.9 | 28.1 | 24.0 | 26.5 | 23.6 | 22.5
Montana | 26.0 | 38.3 | 25.2 | 28.7 | 21.5 | * | 21.2 | 20.2
Nebraska | 29.4 | 31.9 | 29.6 | 27.3 | 22.9 | 24.2 | 23.6 | 19.8
Nevada | 33.5 | 39.0 | 32.1 | 32.5 | 28.1 | 30.9 | 27.0 | 27.4
New Hampshire | 32.9 | 42.1 | 32.3 | 34.5 | 27.5 | 33.3 | 26.9 | 32.8
New Jersey | 33.1 | 37.6 | 30.4 | 34.1 | 27.3 | 31.7 | 26.5 | 25.4
New Mexico | 28.4 | 31.2 | 27.8 | 28.6 | 23.6 | 29.1 | 24.1 | 23.1
New York | 33.9 | 39.2 | 31.3 | 35.7 | 29.6 | 33.9 | 28.3 | 29.6
North Carolina | 30.7 | 35.0 | 30.2 | 27.3 | 24.9 | 29.1 | 24.2 | 21.9
North Dakota | 26.1 | 34.2 | 25.3 | 26.5 | 19.7 | 38.3 | 18.5 | 22.9
Ohio | 31.4 | 34.0 | 30.9 | 28.9 | 25.7 | 29.3 | 25.0 | 22.5
Oklahoma | 33.1 | 37.4 | 32.8 | 31.2 | 25.7 | 29.9 | 25.5 | 24.3
Oregon | 28.9 | 34.7 | 28.1 | 28.9 | 24.0 | 28.5 | 23.0 | 23.9
Pennsylvania | 31.3 | 32.9 | 30.7 | 31.8 | 25.5 | 26.3 | 25.5 | 23.8
Rhode Island | 33.2 | 35.3 | 33.7 | 32.0 | 28.0 | 31.0 | 28.7 | 24.9
South Carolina | 32.6 | 36.2 | 31.9 | 29.2 | 25.2 | 28.4 | 24.8 | 21.6
South Dakota | 24.4 | 29.6 | 23.2 | 26.0 | 19.1 | 19.3 | 18.2 | 24.0
Tennessee | 32.3 | 35.4 | 32.2 | 27.8 | 26.5 | 30.6 | 26.2 | 22.5
Texas | 34.5 | 39.1 | 33.3 | 34.0 | 27.8 | 31.7 | 26.5 | 27.1
Utah | 24.3 | 31.1 | 22.5 | 28.6 | 20.5 | 33.1 | 18.8 | 23.5
Vermont | 27.5 | 28.5 | 27.3 | 27.0 | 23.7 | * | 23.3 | 20.6
Virginia | 32.3 | 37.4 | 30.9 | 29.7 | 26.2 | 30.1 | 24.9 | 23.8
Washington | 30.0 | 37.2 | 28.4 | 29.0 | 26.2 | 35.6 | 24.5 | 24.6
West Virginia | 34.9 | 40.8 | 34.7 | 37.2 | 29.2 | 29.2 | 29.0 | 32.4
Wisconsin | 27.3 | 28.8 | 27.4 | 26.8 | 22.6 | 24.8 | 22.3 | 21.6
Wyoming | 28.3 | * | 27.6 | 31.4 | 22.8 | * | 22.8 | 23.0
Puerto Rico | 50.6 | 34.6 | 40.7 | 50.8 | 48.9 | * | 39.7 | 49.1
U.S. Virgin Islands | 40.0 | 40.4 | 29.1 | 44.5 | 30.9 | 31.8 | * | *
Guam | 26.6 | * | 28.7 | * | 28.1 | * | * | *
American Samoa | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 28.8 | * | * | * | 24.5 | * | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

--- Data not available.

1 Percentage of all live births by cesarean delivery.

2 Number of singleton, term (37 weeks of gestation or more based on the obstetric estimate), cephalic (head first), cesarean deliveries to women having a first birth per 100 women delivering singleton, term, cephalic, first births.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

5 Includes all people of Hispanic origin of any race; see Technical Notes.

6 Excludes data for the territories.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XIII Method of delivery, by age and race and Hispanic origin of mother: United States, 2023

[Percentages are number of live births with specified method of delivery per 100 live births in specified group]

Race and Hispanic origin of mother and method of delivery | All births^1^ | Method reported | Age of mother | | | | | | | Not stated^2^
Race and Hispanic origin of mother and method of delivery | All births^1^ | Method reported | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54 | Not stated^2^
All races and origins^3^ | Number | | Rate per 100 | | | | | | | Number
Fetal presentation at birth:
Cephalic (head first) | 3,596,017 | 3,400,537 | 94.7 | 96.5 | 96.1 | 95.3 | 94.4 | 93.5 | 92.0 | 6,985
Breech | 3,596,017 | 155,516 | 4.3 | 2.7 | 3.1 | 3.9 | 4.7 | 5.5 | 6.7 | 6,985
Other | 3,596,017 | 32,979 | 0.9 | 0.8 | 0.8 | 0.9 | 0.9 | 1.1 | 1.3 | 6,985
Final route and method of delivery:
Vaginal, spontaneous | 3,596,017 | 2,333,523 | 64.9 | 77.2 | 72.1 | 67.5 | 63.2 | 57.4 | 49.7 | 2,621
Vaginal, forceps | 3,596,017 | 15,349 | 0.4 | 0.5 | 0.4 | 0.4 | 0.4 | 0.4 | 0.4 | 2,621
Vaginal, vacuum | 3,596,017 | 82,628 | 2.3 | 3.5 | 2.6 | 2.3 | 2.3 | 2.0 | 1.8 | 2,621
Cesarean | 3,596,017 | 1,161,896 | 32.3 | 18.9 | 24.9 | 29.8 | 34.1 | 40.2 | 48.1 | 2,621
Cesarean, trial of labor attempted^4^ | 1,161,896 | 324,343 | 28.2 | 49.6 | 38.7 | 31.0 | 25.8 | 21.6 | 20.6 | 9,838
Non-Hispanic, single race^5^
Black:
Fetal presentation at birth:
Cephalic (head first) | 491,494 | 466,035 | 95.0 | 97.0 | 96.3 | 95.6 | 94.6 | 93.3 | 91.4 | 953
Breech | 491,494 | 19,467 | 4.0 | 2.2 | 2.8 | 3.5 | 4.3 | 5.5 | 7.3 | 953
Other | 491,494 | 5,039 | 1.0 | 0.8 | 0.9 | 0.9 | 1.1 | 1.2 | 1.4 | 953
Final route and method of delivery:
Vaginal, spontaneous | 491,494 | 298,465 | 60.8 | 74.9 | 68.5 | 62.8 | 57.7 | 51.4 | 43.5 | 248
Vaginal, forceps | 491,494 | 1,601 | 0.3 | 0.5 | 0.4 | 0.3 | 0.3 | 0.2 | 0.2 | 248
Vaginal, vacuum | 491,494 | 9,578 | 1.9 | 3.5 | 2.5 | 1.9 | 1.6 | 1.5 | 1.2 | 248
Cesarean | 491,494 | 181,602 | 37.0 | 21.1 | 28.6 | 35.0 | 40.4 | 46.9 | 55.1 | 248
Cesarean, trial of labor attempted^4^ | 181,602 | 52,524 | 29.1 | 52.2 | 40.6 | 30.7 | 25.4 | 21.8 | 21.3 | 1,364
White:
Fetal presentation at birth:
Cephalic (head first) | 1,787,051 | 1,682,919 | 94.4 | 96.0 | 95.7 | 94.8 | 94.0 | 93.3 | 92.0 | 3,406
Breech | 1,787,051 | 84,067 | 4.7 | 3.2 | 3.5 | 4.3 | 5.0 | 5.6 | 6.7 | 3,406
Other | 1,787,051 | 16,659 | 0.9 | 0.8 | 0.8 | 0.9 | 0.9 | 1.1 | 1.2 | 3,406
Final route and method of delivery:
Vaginal, spontaneous | 1,787,051 | 1,178,964 | 66.0 | 76.1 | 72.7 | 68.8 | 64.9 | 59.6 | 52.0 | 1,141
Vaginal, forceps | 1,787,051 | 8,500 | 0.5 | 0.5 | 0.5 | 0.5 | 0.5 | 0.4 | 0.5 | 1,141
Vaginal, vacuum | 1,787,051 | 42,497 | 2.4 | 3.9 | 2.8 | 2.4 | 2.3 | 2.0 | 1.8 | 1,141
Cesarean | 1,787,051 | 555,949 | 31.1 | 19.4 | 24.1 | 28.3 | 32.3 | 37.9 | 45.7 | 1,141
Cesarean, trial of labor attempted^4^ | 555,949 | 159,367 | 28.9 | 51.0 | 39.4 | 32.7 | 26.8 | 22.4 | 21.5 | 4,098
Hispanic^6^ | Number | | Rate per 100 | | | | | | | Number
Fetal presentation at birth:
Cephalic (head first) | 945,200 | 900,714 | 95.4 | 96.8 | 96.5 | 95.9 | 94.9 | 93.8 | 92.4 | 1,132
Breech | 945,200 | 35,688 | 3.8 | 2.5 | 2.8 | 3.4 | 4.2 | 5.3 | 6.4 | 1,132
Other | 945,200 | 7,666 | 0.8 | 0.7 | 0.7 | 0.8 | 0.8 | 1.0 | 1.2 | 1,132
Final route and method of delivery:
Vaginal, spontaneous | 945,200 | 620,773 | 65.7 | 79.0 | 73.1 | 67.4 | 62.0 | 55.8 | 50.1 | 324
Vaginal, forceps | 945,200 | 3,137 | 0.3 | 0.5 | 0.4 | 0.3 | 0.3 | 0.3 | 0.3 | 324
Vaginal, vacuum | 945,200 | 18,444 | 2.0 | 3.1 | 2.3 | 1.9 | 1.7 | 1.6 | 1.4 | 324
Cesarean | 945,200 | 302,522 | 32.0 | 17.4 | 24.2 | 30.4 | 36.0 | 42.4 | 48.2 | 324
Cesarean, trial of labor attempted^4^ | 302,522 | 76,461 | 25.5 | 46.6 | 36.2 | 26.9 | 21.6 | 18.6 | 18.1 | 3,067

1 Total for vaginal birth after cesarean delivery is the number of births to women delivering after a previous cesarean. Total for primary cesarean is the number of births to women delivering without a previous cesarean. Total for cesarean, trial of labor is the number of women delivering by cesarean after attempting vaginal delivery.

2 No response reported for selected characteristic.

3 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

4 Number of women who attempted a trial of labor prior to cesarean delivery per 100 cesarean births.

5 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

6 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XIV Maternal morbidity, by age and race and Hispanic origin of mother: United States, 2023

[Rates are number of live births with morbidty per 100,000 live births in specified group]

Race and Hispanic origin of mother and maternal morbidity | All births | Morbidity reported | Age of mother | | | | | | | Not stated^1^
Race and Hispanic origin of mother and maternal morbidity | All births | Morbidity reported | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54 | Not stated^1^
All races and origins^2^ | Number | | Rate per 100,000 | | | | | | | Number
Maternal transfusion | 3,596,017 | 21,040 | 586.3 | 757.8 | 556.8 | 524.4 | 553.3 | 669.8 | 861.8 | 7,356
Third- or fourth-degree perineal laceration | 3,596,017 | 28,068 | 782.1 | 784.5 | 717.5 | 846.8 | 873.7 | 657.6 | 445.9 | 7,356
Ruptured uterus | 3,596,017 | 1,486 | 41.4 | 15.4 | 25.2 | 35.5 | 48.5 | 54.0 | 69.5 | 7,356
Unplanned hysterectomy | 3,596,017 | 1,764 | 49.2 | 7.7 | 16.7 | 34.0 | 51.5 | 86.4 | 156.8 | 7,356
Admission to intensive care unit | 3,596,017 | 6,652 | 185.4 | 171.2 | 133.3 | 144.9 | 186.2 | 251.6 | 409.8 | 7,356
Non-Hispanic, single race^3^
Black:
Maternal transfusion | 491,494 | 3,732 | 761.4 | 735.0 | 676.8 | 675.4 | 762.5 | 908.9 | 1,205.2 | 1,326
Third- or fourth-degree perineal laceration | 491,494 | 2,129 | 434.3 | 679.5 | 517.3 | 477.4 | 363.0 | 336.6 | 220.8 | 1,326
Ruptured uterus | 491,494 | 282 | 57.5 | * | 36.0 | 54.1 | 77.8 | 60.6 | 110.4 | 1,326
Unplanned hysterectomy | 491,494 | 281 | 57.3 | * | 13.6 | 44.2 | 67.1 | 109.1 | 170.2 | 1,326
Admission to intensive care unit | 491,494 | 1,393 | 284.2 | 221.9 | 159.5 | 210.2 | 326.4 | 420.1 | 685.4 | 1,326
White:
Maternal transfusion | 1,787,051 | 9,970 | 558.9 | 743.3 | 511.6 | 514.6 | 532.5 | 634.9 | 829.8 | 3,176
Third- or fourth-degree perineal laceration | 1,787,051 | 15,546 | 871.5 | 792.0 | 807.0 | 984.5 | 939.9 | 706.6 | 498.5 | 3,176
Ruptured uterus | 1,787,051 | 717 | 40.2 | * | 25.8 | 34.6 | 42.5 | 54.8 | 68.7 | 3,176
Unplanned hysterectomy | 1,787,051 | 838 | 47.0 | * | 14.8 | 32.0 | 49.6 | 80.0 | 137.3 | 3,176
Admission to intensive care unit | 1,787,051 | 2,811 | 157.6 | 148.2 | 121.5 | 128.2 | 154.4 | 202.2 | 344.8 | 3,176
Hispanic^4^
Maternal transfusion | 945,200 | 4,944 | 523.8 | 738.4 | 527.4 | 444.2 | 486.0 | 606.6 | 699.8 | 1,397
Third- or fourth-degree perineal laceration | 945,200 | 4,917 | 521.0 | 791.3 | 650.3 | 539.4 | 460.2 | 333.3 | 289.3 | 1,397
Ruptured uterus | 945,200 | 298 | 31.6 | 18.8 | 18.3 | 27.0 | 40.0 | 47.2 | 49.6 | 1,397
Unplanned hysterectomy | 945,200 | 421 | 44.6 | * | 20.7 | 28.5 | 51.2 | 87.5 | 154.3 | 1,397
Admission to intensive care unit | 945,200 | 1,587 | 168.1 | 167.1 | 129.2 | 133.4 | 175.3 | 243.5 | 330.6 | 1,397

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 No response reported for selected characteristic.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XV Preterm births, by race and Hispanic origin of mother: United States, each state and territory, 2023

[By place of residence. Preterm is less than 37 completed weeks of gestation based on the obstetric estimate; see Technical Notes in this report]

Area | All races and origins^2^ | Non-Hispanic, single race^1^ | | Hispanic^3^ | All races and origins^2^ | Non-Hispanic, single race^1^ | | Hispanic^3^
Area | All races and origins^2^ | Black | White | Hispanic^3^ | All races and origins^2^ | Black | White | Hispanic^3^
| Number | | | | Percent
United States^4^ | 373,902 | 71,956 | 168,654 | 95,755 | 10.41 | 14.65 | 9.44 | 10.14
Alabama | 7,469 | 2,570 | 3,902 | 711 | 12.91 | 16.54 | 11.74 | 10.33
Alaska | 925 | 25 | 346 | 73 | 10.27 | 11.79 | 7.95 | 9.21
Arizona | 7,701 | 547 | 2,673 | 3,517 | 9.87 | 12.64 | 9.01 | 10.00
Arkansas | 4,259 | 1,054 | 2,489 | 439 | 12.09 | 16.55 | 11.24 | 10.20
California | 36,642 | 2,412 | 8,008 | 18,473 | 9.16 | 13.16 | 7.68 | 9.48
Colorado | 5,962 | 413 | 3,073 | 1,927 | 9.70 | 14.23 | 9.14 | 9.87
Connecticut | 3,226 | 584 | 1,433 | 971 | 9.34 | 14.43 | 7.98 | 9.91
Delaware | 1,088 | 352 | 438 | 200 | 10.44 | 13.07 | 9.32 | 9.93
District of Columbia | 850 | 495 | 168 | 148 | 10.77 | 14.73 | 6.54 | 10.48
Florida | 23,732 | 6,615 | 8,698 | 7,373 | 10.72 | 14.74 | 9.66 | 9.71
Georgia | 14,785 | 6,124 | 5,440 | 2,239 | 11.82 | 14.90 | 10.36 | 10.18
Hawaii | 1,488 | 38 | 234 | 249 | 10.05 | 12.18 | 8.34 | 9.54
Idaho | 1,942 | 32 | 1,408 | 399 | 8.68 | 11.03 | 8.46 | 9.36
Illinois | 13,422 | 2,759 | 6,334 | 3,206 | 10.76 | 15.33 | 9.80 | 10.53
Indiana | 8,714 | 1,479 | 5,655 | 1,067 | 11.04 | 14.75 | 10.50 | 10.08
Iowa | 3,733 | 371 | 2,660 | 445 | 10.36 | 14.21 | 9.88 | 10.58
Kansas | 3,559 | 338 | 2,342 | 654 | 10.45 | 15.29 | 10.15 | 9.95
Kentucky | 5,861 | 720 | 4,360 | 516 | 11.28 | 14.59 | 10.99 | 10.64
Louisiana | 7,333 | 3,394 | 3,062 | 632 | 13.36 | 17.31 | 11.25 | 10.61
Maine | 1,111 | 79 | 957 | 35 | 9.57 | 10.01 | 9.57 | 10.51
Maryland | 6,714 | 2,462 | 2,219 | 1,441 | 10.24 | 13.01 | 8.62 | 9.99
Massachusetts | 6,057 | 817 | 3,047 | 1,524 | 9.06 | 11.20 | 8.46 | 9.71
Michigan | 10,212 | 2,563 | 6,136 | 759 | 10.31 | 15.72 | 9.06 | 10.05
Minnesota | 5,823 | 881 | 3,570 | 615 | 9.44 | 11.88 | 8.84 | 9.47
Mississippi | 5,151 | 2,541 | 2,223 | 235 | 14.96 | 18.30 | 12.81 | 11.07
Missouri | 7,402 | 1,368 | 4,991 | 509 | 11.04 | 16.09 | 10.29 | 9.23
Montana | 1,037 | * | 791 | 79 | 9.37 | * | 8.91 | 11.24
Nebraska | 2,681 | 208 | 1,629 | 577 | 11.12 | 13.82 | 10.41 | 11.52
Nevada | 3,518 | 615 | 997 | 1,338 | 11.07 | 15.03 | 9.55 | 10.59
New Hampshire | 992 | 34 | 833 | 72 | 8.32 | 11.18 | 8.26 | 8.11
New Jersey | 9,368 | 1,545 | 3,649 | 3,000 | 9.28 | 12.84 | 7.90 | 9.92
New Mexico | 2,116 | 43 | 503 | 1,259 | 10.11 | 11.29 | 9.62 | 10.11
New York | 19,544 | 3,604 | 8,359 | 5,238 | 9.62 | 13.76 | 8.25 | 10.31
North Carolina | 12,890 | 3,762 | 5,835 | 2,267 | 10.74 | 14.97 | 9.55 | 9.53
North Dakota | 994 | 65 | 671 | 82 | 10.31 | 11.82 | 9.66 | 10.80
Ohio | 13,565 | 2,829 | 8,779 | 1,016 | 10.70 | 14.08 | 9.89 | 10.43
Oklahoma | 5,279 | 549 | 2,725 | 882 | 11.03 | 14.91 | 10.70 | 10.02
Oregon | 3,439 | 101 | 1,946 | 827 | 8.98 | 10.07 | 8.59 | 9.32
Pennsylvania | 12,311 | 2,166 | 7,197 | 1,943 | 9.71 | 13.76 | 8.76 | 10.51
Rhode Island | 938 | 90 | 473 | 294 | 9.57 | 11.31 | 8.98 | 9.77
South Carolina | 6,701 | 2,310 | 3,174 | 817 | 11.61 | 15.67 | 9.96 | 10.27
South Dakota | 1,401 | 49 | 939 | 101 | 12.52 | 14.20 | 11.73 | 12.11
Tennessee | 9,408 | 2,200 | 5,644 | 1,179 | 11.34 | 15.31 | 10.66 | 9.92
Texas | 43,172 | 6,994 | 11,651 | 21,527 | 11.13 | 14.84 | 9.78 | 11.22
Utah | 4,218 | 72 | 2,825 | 948 | 9.37 | 11.04 | 8.93 | 10.27
Vermont | 388 | * | 350 | 12 | 7.66 | * | 7.74 | 7.89
Virginia | 9,076 | 2,358 | 4,330 | 1,474 | 9.80 | 13.40 | 8.81 | 9.09
Washington | 7,026 | 367 | 3,361 | 1,567 | 8.70 | 10.06 | 7.98 | 9.16
West Virginia | 2,172 | 95 | 1,914 | 61 | 13.09 | 16.58 | 12.89 | 12.06
Wisconsin | 5,922 | 849 | 3,802 | 735 | 9.92 | 15.21 | 9.18 | 9.70
Wyoming | 585 | * | 411 | 103 | 9.77 | * | 9.03 | 12.00
Puerto Rico | 2,273 | * | 26 | 2,237 | 12.22 | * | 7.14 | 12.33
U.S. Virgin Islands | 107 | 77 | * | 26 | 13.11 | 14.05 | * | 15.76
Guam | 312 | * | 14 | * | 13.33 | * | 12.17 | *
American Samoa | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 60 | * | * | * | 10.38 | * | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

--- Data not available.

1 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

4 Excludes data for the territories.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XVI Late preterm births, by race and Hispanic origin of mother: United States, each state and territory, 2023

[By place of residence. Late preterm is 34–36 completed weeks of gestation based on the obstetric estimate; see Technical Notes in this report]

Area | All races and origins^2^ | Non-Hispanic, single race^1^ | | Hispanic^3^ | All races and origins^2^ | Non-Hispanic, single race^1^ | | Hispanic^3^
Area | All races and origins^2^ | Black | White | Hispanic^3^ | All races and origins^2^ | Black | White | Hispanic^3^
| Number | | | | Percent
United States^4^ | 274,647 | 48,097 | 127,918 | 71,020 | 7.64 | 9.79 | 7.16 | 7.52
Alabama | 5,500 | 1,748 | 3,003 | 524 | 9.51 | 11.25 | 9.04 | 7.61
Alaska | 709 | 20 | 274 | 57 | 7.87 | 9.43 | 6.30 | 7.19
Arizona | 5,713 | 359 | 2,031 | 2,615 | 7.32 | 8.30 | 6.85 | 7.44
Arkansas | 3,132 | 724 | 1,858 | 351 | 8.89 | 11.37 | 8.39 | 8.16
California | 27,138 | 1,623 | 6,133 | 13,666 | 6.79 | 8.86 | 5.88 | 7.02
Colorado | 4,424 | 275 | 2,291 | 1,445 | 7.20 | 9.48 | 6.81 | 7.40
Connecticut | 2,302 | 372 | 1,075 | 690 | 6.66 | 9.19 | 5.98 | 7.04
Delaware | 795 | 218 | 358 | 151 | 7.63 | 8.09 | 7.62 | 7.49
District of Columbia | 574 | 317 | 127 | 106 | 7.27 | 9.43 | 4.95 | 7.51
Florida | 17,142 | 4,337 | 6,569 | 5,470 | 7.75 | 9.67 | 7.29 | 7.20
Georgia | 10,740 | 4,158 | 4,164 | 1,678 | 8.59 | 10.12 | 7.93 | 7.63
Hawaii | 1,112 | 30 | 181 | 193 | 7.51 | 9.62 | 6.45 | 7.40
Idaho | 1,459 | 24 | 1,072 | 281 | 6.52 | 8.28 | 6.44 | 6.59
Illinois | 9,785 | 1,814 | 4,794 | 2,337 | 7.84 | 10.08 | 7.41 | 7.67
Indiana | 6,482 | 988 | 4,300 | 809 | 8.21 | 9.85 | 7.99 | 7.64
Iowa | 2,773 | 250 | 1,984 | 347 | 7.70 | 9.57 | 7.37 | 8.25
Kansas | 2,715 | 236 | 1,807 | 498 | 7.97 | 10.68 | 7.83 | 7.58
Kentucky | 4,375 | 492 | 3,310 | 382 | 8.42 | 9.97 | 8.35 | 7.88
Louisiana | 5,408 | 2,326 | 2,399 | 491 | 9.85 | 11.86 | 8.82 | 8.24
Maine | 841 | 58 | 729 | 27 | 7.24 | 7.35 | 7.29 | 8.11
Maryland | 4,840 | 1,615 | 1,688 | 1,079 | 7.38 | 8.53 | 6.56 | 7.48
Massachusetts | 4,501 | 555 | 2,311 | 1,144 | 6.73 | 7.61 | 6.42 | 7.29
Michigan | 7,425 | 1,700 | 4,581 | 587 | 7.49 | 10.42 | 6.77 | 7.77
Minnesota | 4,291 | 574 | 2,727 | 446 | 6.96 | 7.74 | 6.75 | 6.87
Mississippi | 3,735 | 1,728 | 1,730 | 171 | 10.84 | 12.45 | 9.97 | 8.06
Missouri | 5,528 | 911 | 3,826 | 391 | 8.24 | 10.71 | 7.89 | 7.09
Montana | 794 | * | 603 | 60 | 7.17 | * | 6.79 | 8.53
Nebraska | 2,025 | 143 | 1,233 | 447 | 8.40 | 9.50 | 7.88 | 8.92
Nevada | 2,547 | 440 | 761 | 954 | 8.01 | 10.75 | 7.29 | 7.55
New Hampshire | 743 | 26 | 632 | 47 | 6.23 | 8.55 | 6.26 | 5.29
New Jersey | 7,004 | 999 | 2,881 | 2,253 | 6.94 | 8.30 | 6.24 | 7.45
New Mexico | 1,557 | 30 | 358 | 914 | 7.44 | 7.87 | 6.85 | 7.34
New York | 14,498 | 2,398 | 6,448 | 3,863 | 7.14 | 9.16 | 6.37 | 7.60
North Carolina | 9,215 | 2,484 | 4,356 | 1,661 | 7.68 | 9.89 | 7.13 | 6.99
North Dakota | 773 | 41 | 525 | 70 | 8.02 | 7.45 | 7.56 | 9.22
Ohio | 9,733 | 1,892 | 6,420 | 758 | 7.67 | 9.42 | 7.23 | 7.78
Oklahoma | 3,913 | 360 | 2,039 | 651 | 8.18 | 9.78 | 8.01 | 7.40
Oregon | 2,577 | 72 | 1,477 | 609 | 6.73 | 7.18 | 6.52 | 6.86
Pennsylvania | 8,911 | 1,437 | 5,413 | 1,357 | 7.03 | 9.13 | 6.59 | 7.34
Rhode Island | 710 | 57 | 366 | 224 | 7.24 | 7.16 | 6.95 | 7.45
South Carolina | 4,803 | 1,561 | 2,381 | 598 | 8.32 | 10.59 | 7.47 | 7.52
South Dakota | 1,090 | 30 | 750 | 78 | 9.74 | 8.70 | 9.37 | 9.35
Tennessee | 6,971 | 1,469 | 4,316 | 907 | 8.40 | 10.22 | 8.15 | 7.63
Texas | 31,613 | 4,736 | 8,779 | 15,944 | 8.15 | 10.05 | 7.37 | 8.31
Utah | 3,141 | 42 | 2,129 | 712 | 6.98 | 6.44 | 6.73 | 7.71
Vermont | 293 | * | 265 | * | 5.79 | * | 5.86 | *
Virginia | 6,537 | 1,531 | 3,282 | 1,089 | 7.06 | 8.70 | 6.68 | 6.71
Washington | 5,254 | 237 | 2,533 | 1,199 | 6.51 | 6.50 | 6.01 | 7.01
West Virginia | 1,642 | 67 | 1,456 | 48 | 9.89 | 11.69 | 9.81 | 9.49
Wisconsin | 4,397 | 580 | 2,867 | 550 | 7.37 | 10.39 | 6.92 | 7.26
Wyoming | 467 | * | 326 | 84 | 7.80 | * | 7.16 | 9.79
Puerto Rico | 1,654 | * | 14 | 1,634 | 8.89 | * | 3.85 | 9.01
U.S. Virgin Islands | 86 | 62 | * | 20 | 10.54 | 11.31 | * | 12.12
Guam | 242 | * | 13 | * | 10.34 | * | 11.30 | *
American Samoa | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 43 | * | * | * | 7.44 | * | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

--- Data not available.

1 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

4 Excludes data for the territories.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XVII Low birthweight births, by race and Hispanic origin of mother: United States, each state and territory, 2023

[By place of residence. Low birth weight is less than 2,500 grams]

Area | All races and origins^2^ | Non-Hispanic, single race^1^ | | Hispanic^3^ | All races and origins^2^ | Non-Hispanic, single race^1^ | | Hispanic^3^
Area | All races and origins^2^ | Black | White | Hispanic^3^ | All races and origins^2^ | Black | White | Hispanic^3^
| Number | | | | Percent
United States^4^ | 308,263 | 72,673 | 125,668 | 74,860 | 8.58 | 14.80 | 7.04 | 7.92
Alabama | 6,032 | 2,569 | 2,652 | 564 | 10.43 | 16.55 | 7.98 | 8.19
Alaska | 602 | 26 | 218 | 55 | 6.68 | 12.26 | 5.01 | 6.94
Arizona | 6,291 | 558 | 2,126 | 2,757 | 8.06 | 12.90 | 7.16 | 7.84
Arkansas | 3,399 | 1,025 | 1,802 | 327 | 9.65 | 16.11 | 8.14 | 7.60
California | 30,056 | 2,408 | 6,183 | 14,275 | 7.51 | 13.13 | 5.92 | 7.32
Colorado | 5,973 | 455 | 3,016 | 1,865 | 9.74 | 15.72 | 8.99 | 9.56
Connecticut | 2,732 | 553 | 1,072 | 853 | 7.91 | 13.67 | 5.97 | 8.71
Delaware | 954 | 374 | 331 | 149 | 9.15 | 13.89 | 7.04 | 7.39
District of Columbia | 855 | 535 | 148 | 121 | 10.83 | 15.91 | 5.76 | 8.56
Florida | 20,003 | 6,631 | 6,523 | 5,839 | 9.04 | 14.78 | 7.24 | 7.69
Georgia | 12,730 | 6,276 | 3,836 | 1,667 | 10.18 | 15.28 | 7.30 | 7.58
Hawaii | 1,290 | 36 | 181 | 212 | 8.71 | 11.50 | 6.45 | 8.12
Idaho | 1,550 | 26 | 1,085 | 352 | 6.93 | 8.97 | 6.52 | 8.26
Illinois | 11,071 | 2,880 | 4,604 | 2,472 | 8.87 | 16.01 | 7.12 | 8.12
Indiana | 6,787 | 1,427 | 4,006 | 884 | 8.60 | 14.24 | 7.44 | 8.36
Iowa | 2,742 | 349 | 1,837 | 326 | 7.61 | 13.37 | 6.82 | 7.75
Kansas | 2,604 | 335 | 1,585 | 488 | 7.65 | 15.15 | 6.87 | 7.42
Kentucky | 4,597 | 740 | 3,216 | 378 | 8.85 | 15.02 | 8.11 | 7.79
Louisiana | 6,176 | 3,352 | 2,137 | 478 | 11.25 | 17.10 | 7.85 | 8.02
Maine | 932 | 68 | 796 | 30 | 8.02 | 8.62 | 7.95 | 8.98
Maryland | 5,623 | 2,429 | 1,614 | 1,026 | 8.58 | 12.83 | 6.27 | 7.11
Massachusetts | 5,081 | 794 | 2,331 | 1,269 | 7.61 | 10.89 | 6.48 | 8.09
Michigan | 8,827 | 2,652 | 4,808 | 597 | 8.91 | 16.27 | 7.10 | 7.91
Minnesota | 4,439 | 842 | 2,477 | 446 | 7.20 | 11.38 | 6.14 | 6.87
Mississippi | 4,290 | 2,501 | 1,501 | 167 | 12.45 | 18.00 | 8.65 | 7.87
Missouri | 5,972 | 1,423 | 3,674 | 425 | 8.90 | 16.75 | 7.57 | 7.70
Montana | 855 | 11 | 667 | 62 | 7.72 | 18.33 | 7.51 | 8.82
Nebraska | 1,936 | 200 | 1,129 | 402 | 8.03 | 13.30 | 7.21 | 8.02
Nevada | 3,016 | 596 | 780 | 1,124 | 9.49 | 14.57 | 7.47 | 8.90
New Hampshire | 809 | 41 | 649 | 66 | 6.79 | 13.49 | 6.44 | 7.44
New Jersey | 7,875 | 1,536 | 2,771 | 2,338 | 7.80 | 12.77 | 6.00 | 7.73
New Mexico | 2,024 | 48 | 498 | 1,199 | 9.66 | 12.60 | 9.52 | 9.62
New York | 17,381 | 3,712 | 6,749 | 4,429 | 8.55 | 14.18 | 6.66 | 8.72
North Carolina | 11,297 | 3,940 | 4,467 | 1,849 | 9.42 | 15.69 | 7.31 | 7.78
North Dakota | 681 | 66 | 417 | 58 | 7.06 | 12.02 | 6.00 | 7.64
Ohio | 11,092 | 2,958 | 6,463 | 810 | 8.75 | 14.74 | 7.28 | 8.32
Oklahoma | 4,117 | 572 | 2,029 | 669 | 8.60 | 15.54 | 7.97 | 7.60
Oregon | 2,740 | 107 | 1,487 | 650 | 7.16 | 10.67 | 6.56 | 7.32
Pennsylvania | 10,703 | 2,234 | 5,741 | 1,678 | 8.44 | 14.18 | 6.98 | 9.08
Rhode Island | 753 | 86 | 359 | 241 | 7.69 | 10.82 | 6.82 | 8.01
South Carolina | 5,750 | 2,441 | 2,293 | 644 | 9.96 | 16.57 | 7.19 | 8.09
South Dakota | 807 | 40 | 529 | 60 | 7.21 | 11.59 | 6.61 | 7.18
Tennessee | 7,526 | 2,231 | 4,071 | 846 | 9.07 | 15.53 | 7.69 | 7.11
Texas | 33,329 | 6,596 | 8,102 | 15,827 | 8.60 | 14.01 | 6.80 | 8.25
Utah | 3,308 | 76 | 2,150 | 767 | 7.35 | 11.69 | 6.80 | 8.31
Vermont | 359 | * | 327 | 11 | 7.09 | * | 7.23 | 7.24
Virginia | 7,812 | 2,505 | 3,269 | 1,157 | 8.44 | 14.24 | 6.65 | 7.13
Washington | 5,633 | 369 | 2,481 | 1,222 | 6.97 | 10.13 | 5.89 | 7.14
West Virginia | 1,628 | 94 | 1,404 | 42 | 9.81 | 16.40 | 9.46 | 8.30
Wisconsin | 4,685 | 938 | 2,687 | 597 | 7.85 | 16.80 | 6.48 | 7.87
Wyoming | 539 | * | 390 | 90 | 9.01 | * | 8.58 | 10.50
Puerto Rico | 1,995 | * | 36 | 1,950 | 10.73 | * | 9.89 | 10.75
U.S. Virgin Islands | 88 | 68 | * | 15 | 10.77 | 12.43 | * | 9.09
Guam | 255 | * | * | * | 10.86 | * | * | *
American Samoa | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 61 | * | * | * | 10.54 | * | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

--- Data not available.

1 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

4 Excludes data for the territories.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XVIII Very low birthweight births, by race and Hispanic origin of mother: United States, each state and territory, 2023

[By place of residence. Very low birthweight is less than 1,500 grams]

Area | All races and origins^2^ | Non-Hispanic, single race^1^ | | Hispanic^3^ | All races and origins^2^ | Non-Hispanic, single race^1^ | | Hispanic^3^
Area | All races and origins^2^ | Black | White | Hispanic^3^ | All races and origins^2^ | Black | White | Hispanic^3^
| Number | | | | Percent
United States^4^ | 48,832 | 14,048 | 17,914 | 11,932 | 1.36 | 2.86 | 1.00 | 1.26
Alabama | 1,096 | 521 | 440 | 103 | 1.90 | 3.36 | 1.32 | 1.49
Alaska | 89 | * | 32 | 13 | 0.99 | * | 0.74 | 1.64
Arizona | 970 | 102 | 321 | 427 | 1.24 | 2.36 | 1.08 | 1.21
Arkansas | 574 | 203 | 294 | 36 | 1.63 | 3.19 | 1.33 | 0.84
California | 4,532 | 472 | 821 | 2,248 | 1.13 | 2.57 | 0.79 | 1.15
Colorado | 731 | 86 | 340 | 230 | 1.19 | 2.97 | 1.01 | 1.18
Connecticut | 444 | 122 | 154 | 130 | 1.29 | 3.02 | 0.86 | 1.33
Delaware | 157 | 82 | 35 | 28 | 1.51 | 3.04 | 0.74 | 1.39
District of Columbia | 143 | 102 | 14 | 18 | 1.81 | 3.03 | 0.54 | 1.27
Florida | 3,526 | 1,385 | 1,000 | 995 | 1.59 | 3.09 | 1.11 | 1.31
Georgia | 2,109 | 1,182 | 520 | 290 | 1.69 | 2.88 | 0.99 | 1.32
Hawaii | 190 | * | 31 | 31 | 1.28 | * | 1.10 | 1.19
Idaho | 231 | * | 153 | 59 | 1.03 | * | 0.92 | 1.38
Illinois | 1,724 | 553 | 597 | 428 | 1.38 | 3.07 | 0.92 | 1.41
Indiana | 1,065 | 288 | 583 | 123 | 1.35 | 2.87 | 1.08 | 1.16
Iowa | 412 | 66 | 261 | 50 | 1.14 | 2.53 | 0.97 | 1.19
Kansas | 359 | 61 | 208 | 68 | 1.05 | 2.76 | 0.90 | 1.03
Kentucky | 730 | 128 | 489 | 69 | 1.40 | 2.60 | 1.23 | 1.42
Louisiana | 1,067 | 664 | 306 | 74 | 1.94 | 3.39 | 1.12 | 1.24
Maine | 121 | 16 | 98 | * | 1.04 | 2.03 | 0.98 | *
Maryland | 968 | 487 | 241 | 176 | 1.48 | 2.57 | 0.94 | 1.22
Massachusetts | 749 | 147 | 320 | 193 | 1.12 | 2.02 | 0.89 | 1.23
Michigan | 1,340 | 485 | 670 | 80 | 1.35 | 2.98 | 0.99 | 1.06
Minnesota | 725 | 172 | 362 | 73 | 1.18 | 2.32 | 0.90 | 1.12
Mississippi | 735 | 462 | 220 | 32 | 2.13 | 3.33 | 1.27 | 1.51
Missouri | 894 | 250 | 507 | 70 | 1.33 | 2.94 | 1.05 | 1.27
Montana | 113 | * | 83 | 12 | 1.02 | * | 0.93 | 1.71
Nebraska | 295 | 30 | 168 | 61 | 1.22 | 1.99 | 1.07 | 1.22
Nevada | 445 | 99 | 94 | 178 | 1.40 | 2.42 | 0.90 | 1.41
New Hampshire | 101 | * | 77 | 12 | 0.85 | * | 0.76 | 1.35
New Jersey | 1,176 | 298 | 336 | 377 | 1.16 | 2.48 | 0.73 | 1.25
New Mexico | 245 | * | 55 | 159 | 1.17 | * | 1.05 | 1.28
New York | 2,493 | 729 | 819 | 662 | 1.23 | 2.78 | 0.81 | 1.30
North Carolina | 1,937 | 795 | 674 | 308 | 1.61 | 3.17 | 1.10 | 1.30
North Dakota | 115 | 12 | 69 | * | 1.19 | 2.19 | 0.99 | *
Ohio | 1,895 | 560 | 1,062 | 132 | 1.49 | 2.79 | 1.20 | 1.36
Oklahoma | 654 | 107 | 288 | 126 | 1.37 | 2.91 | 1.13 | 1.43
Oregon | 411 | 21 | 223 | 91 | 1.07 | 2.09 | 0.98 | 1.02
Pennsylvania | 1,665 | 426 | 775 | 301 | 1.31 | 2.70 | 0.94 | 1.63
Rhode Island | 124 | 19 | 52 | 47 | 1.27 | 2.39 | 0.99 | 1.56
South Carolina | 941 | 448 | 328 | 100 | 1.63 | 3.04 | 1.03 | 1.26
South Dakota | 143 | 10 | 86 | 12 | 1.28 | 2.90 | 1.08 | 1.44
Tennessee | 1,244 | 437 | 614 | 139 | 1.50 | 3.04 | 1.16 | 1.17
Texas | 5,404 | 1,231 | 1,174 | 2,567 | 1.39 | 2.61 | 0.99 | 1.34
Utah | 497 | 20 | 324 | 109 | 1.10 | 3.08 | 1.02 | 1.18
Vermont | 44 | * | 39 | * | 0.87 | * | 0.86 | *
Virginia | 1,330 | 491 | 490 | 213 | 1.44 | 2.79 | 1.00 | 1.31
Washington | 841 | 75 | 395 | 167 | 1.04 | 2.06 | 0.94 | 0.98
West Virginia | 250 | 13 | 217 | * | 1.51 | 2.27 | 1.46 | *
Wisconsin | 728 | 162 | 416 | 82 | 1.22 | 2.90 | 1.00 | 1.08
Wyoming | 60 | * | 39 | 12 | 1.00 | * | 0.86 | 1.40
Puerto Rico | 304 | * | * | 296 | 1.63 | * | * | 1.63
U.S. Virgin Islands | 10 | * | * | * | 1.22 | * | * | *
Guam | 30 | * | * | * | 1.28 | * | * | *
American Samoa | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | * | * | * | * | * | * | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

--- Data not available.

1 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

4 Excludes data for the territories.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XIX Twin and triplet or higher-order multiple births, by state: United States and each state, 2021–2023

Area | Twin | | Area | Triplet or higher order^1^
Area | Number | Rate per 1,000 live births | Area | Number | Rate per 100,000 live births
United States | 339,037 | 31.0 | United States | 8,481 | 77.6
Alabama | 5,964 | 34.3 | Alabama | 158 | 90.8
Alaska | 853 | 30.7 | Alaska | 27 | 97.3
Arizona | 6,910 | 29.5 | Arizona | 164 | 69.9
Arkansas | 3,221 | 30.2 | Arkansas | 53 | 49.7
California | 35,181 | 28.4 | California | 775 | 62.5
Colorado | 5,464 | 29.2 | Colorado | 120 | 64.2
Connecticut | 3,705 | 35.1 | Connecticut | 84 | 79.6
Delaware | 927 | 29.2 | Delaware | 36 | 113.5
District of Columbia | 749 | 30.4 | District of Columbia | 12 | 48.7
Florida | 19,608 | 29.6 | Florida | 410 | 61.9
Georgia | 12,382 | 33.0 | Georgia | 304 | 81.0
Hawaii | 1,321 | 28.7 | Hawaii | 17 | 37.0
Idaho | 1,997 | 29.7 | Idaho | 66 | 98.2
Illinois | 12,661 | 32.9 | Illinois | 265 | 68.8
Indiana | 7,988 | 33.5 | Indiana | 225 | 94.3
Iowa | 3,783 | 34.6 | Iowa | 99 | 90.5
Kansas | 3,189 | 30.9 | Kansas | 80 | 77.5
Kentucky | 4,951 | 31.6 | Kentucky | 123 | 78.6
Louisiana | 5,522 | 32.7 | Louisiana | 149 | 88.2
Maine | 1,198 | 33.5 | Maine | 12 | 33.6
Maryland | 6,114 | 30.2 | Maryland | 159 | 78.5
Massachusetts | 6,707 | 32.7 | Massachusetts | 178 | 86.9
Michigan | 10,980 | 35.8 | Michigan | 262 | 85.5
Minnesota | 6,278 | 33.0 | Minnesota | 204 | 107.3
Mississippi | 3,682 | 35.3 | Mississippi | 119 | 114.1
Missouri | 6,838 | 33.3 | Missouri | 160 | 77.8
Montana | 974 | 29.1 | Montana | 24 | 71.7
Nebraska | 2,404 | 32.9 | Nebraska | 116 | 158.8
Nevada | 3,054 | 31.0 | Nevada | 76 | 77.0
New Hampshire | 1,199 | 32.7 | New Hampshire | 20 | 54.6
New Jersey | 9,221 | 30.2 | New Jersey | 245 | 80.2
New Mexico | 1,665 | 26.0 | New Mexico | 27 | 42.2
New York | 19,522 | 31.4 | New York | 528 | 84.9
North Carolina | 11,471 | 31.7 | North Carolina | 281 | 77.6
North Dakota | 870 | 29.7 | North Dakota | 32 | 109.1
Ohio | 12,473 | 32.4 | Ohio | 293 | 76.1
Oklahoma | 4,440 | 30.7 | Oklahoma | 113 | 78.1
Oregon | 3,754 | 31.6 | Oregon | 78 | 65.7
Pennsylvania | 12,335 | 31.6 | Pennsylvania | 328 | 84.1
Rhode Island | 894 | 29.3 | Rhode Island | 24 | 78.6
South Carolina | 5,559 | 32.2 | South Carolina | 146 | 84.5
South Dakota | 1,144 | 33.9 | South Dakota | 25 | 74.0
Tennessee | 7,715 | 31.2 | Tennessee | 228 | 92.3
Texas | 33,424 | 29.0 | Texas | 954 | 82.9
Utah | 4,368 | 31.8 | Utah | 132 | 96.0
Vermont | 512 | 32.5 | Vermont | * | *
Virginia | 8,654 | 30.5 | Virginia | 194 | 68.3
Washington | 7,222 | 29.1 | Washington | 146 | 58.8
West Virginia | 1,630 | 32.1 | West Virginia | 53 | 104.5
Wisconsin | 5,809 | 32.0 | Wisconsin | 151 | 83.2
Wyoming | 551 | 30.1 | Wyoming | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Includes triplet, quadruplet, and other higher-order multiple births.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XX Abnormal conditions of the newborn, by age and race and Hispanic origin of mother: United States, 2023

[Rates are number of live births with specified condition per 1,000 live births in specified group]

Abnormal condition and race and Hispanic origin of mother | All births | Condition reported | Age of mother | | | | | | | Not stated^1^
Abnormal condition and race and Hispanic origin of mother | All births | Condition reported | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54 | Not stated^1^
All races^2^ | Number | | Rate per 1,000 | | | | | | | Number
Assisted ventilation required immediately following delivery | 3,596,017 | 230,769 | 64.3 | 61.3 | 59.1 | 62.2 | 64.2 | 69.8 | 81.4 | 6,534
Assisted ventilation required for more than 6 hours | 3,596,017 | 75,664 | 21.1 | 20.8 | 19.8 | 20.3 | 20.9 | 22.6 | 27.5 | 6,534
Neonatal intensive care unit admission | 3,596,017 | 351,804 | 98.0 | 98.5 | 90.8 | 92.1 | 96.3 | 108.8 | 135.8 | 6,534
Surfactant replacement therapy given to newborn | 3,596,017 | 18,267 | 5.1 | 5.4 | 4.9 | 4.8 | 5.0 | 5.4 | 6.6 | 6,534
Antibiotics received by newborn for suspected neonatal sepsis | 3,596,017 | 68,477 | 19.1 | 22.4 | 19.6 | 18.6 | 18.4 | 19.1 | 21.8 | 6,534
Seizure or serious neurologic dysfunction | 3,596,017 | 1,319 | 0.4 | 0.4 | 0.4 | 0.4 | 0.4 | 0.3 | 0.4 | 6,534
Non-Hispanic, single race^3^
Black:
Assisted ventilation required immediately following delivery | 491,494 | 37,072 | 75.6 | 68.2 | 67.0 | 71.7 | 77.4 | 86.4 | 101.3 | 894
Assisted ventilation required for more than 6 hours | 491,494 | 12,887 | 26.3 | 22.8 | 23.5 | 25.4 | 26.2 | 30.0 | 37.2 | 894
Neonatal intensive care unit admission | 491,494 | 64,725 | 131.9 | 120.9 | 117.4 | 124.0 | 133.9 | 152.6 | 180.6 | 894
Surfactant replacement therapy given to newborn | 491,494 | 3,375 | 6.9 | 6.3 | 6.1 | 6.5 | 7.2 | 7.7 | 8.7 | 894
Antibiotics received by newborn for suspected neonatal sepsis | 491,494 | 12,265 | 25.0 | 27.2 | 24.6 | 24.5 | 24.3 | 25.8 | 28.9 | 894
Seizure or serious neurologic dysfunction | 491,494 | 179 | 0.4 | 0.3 | 0.5 | 0.3 | 0.4 | 0.3 | 0.6 | 894
White:
Assisted ventilation required immediately following delivery | 1,787,051 | 127,437 | 71.4 | 71.8 | 67.9 | 70.1 | 70.1 | 75.4 | 87.3 | 2,404
Assisted ventilation required for more than 6 hours | 1,787,051 | 41,580 | 23.3 | 25.1 | 22.7 | 22.7 | 22.8 | 24.3 | 28.7 | 2,404
Neonatal intensive care unit admission | 1,787,051 | 168,309 | 94.3 | 94.8 | 88.3 | 89.6 | 92.4 | 103.1 | 128.5 | 2,404
Surfactant replacement therapy given to newborn | 1,787,051 | 9,529 | 5.3 | 6.0 | 5.4 | 5.2 | 5.1 | 5.6 | 6.6 | 2,404
Antibiotics received by newborn for suspected neonatal sepsis | 1,787,051 | 34,321 | 19.2 | 23.1 | 19.8 | 18.9 | 18.7 | 19.3 | 21.9 | 2,404
Seizure or serious neurologic dysfunction | 1,787,051 | 778 | 0.4 | 0.6 | 0.5 | 0.4 | 0.4 | 0.4 | 0.5 | 2,404
Hispanic^4^
Assisted ventilation required immediately following delivery | 945,200 | 43,970 | 46.6 | 47.4 | 42.6 | 43.4 | 47.5 | 53.1 | 63.3 | 1,867
Assisted ventilation required for more than 6 hours | 945,200 | 14,475 | 15.3 | 15.5 | 14.0 | 13.9 | 15.7 | 17.8 | 22.8 | 1,867
Neonatal intensive care unit admission | 945,200 | 83,566 | 88.6 | 90.4 | 80.3 | 81.1 | 89.4 | 103.7 | 128.9 | 1,867
Surfactant replacement therapy given to newborn | 945,200 | 3,748 | 4.0 | 4.3 | 3.5 | 3.5 | 4.1 | 4.7 | 6.0 | 1,867
Antibiotics received by newborn for suspected neonatal sepsis | 945,200 | 15,017 | 15.9 | 19.3 | 16.6 | 14.9 | 15.1 | 16.3 | 18.7 | 1,867
Seizure or serious neurologic dysfunction | 945,200 | 247 | 0.3 | 0.3 | 0.3 | 0.3 | 0.2 | 0.3 | * | 1,867

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 No response reported for selected characteristic.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origins not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table XXI Congenital anomalies of the newborn, by age of mother: United States, 2023

[Rates are number of live births with specified anomalies per 100,000 live births in specified group]

Congenital anomaly | All births | Congenital anomalies reported | Age of mother | | | | | | | Not stated^1^
Congenital anomaly | All births | Congenital anomalies reported | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54 | Not stated^1^
| Number | | Rate per 100,000 | | | | | | | Number
Anencephaly | 3,596,017 | 340 | 9.5 | 11.2 | 11.5 | 9.0 | 8.9 | 8.6 | 10.2 | 8,211
Meningomyelocele or spina bifida | 3,596,017 | 445 | 12.4 | 11.9 | 11.9 | 12.5 | 12.3 | 11.9 | 17.1 | 8,211
Cyanotic congenital heart disease | 3,596,017 | 2,271 | 63.3 | 57.5 | 58.0 | 62.6 | 55.7 | 72.3 | 115.9 | 8,211
Congenital diaphragmatic hernia | 3,596,017 | 473 | 13.2 | 18.9 | 14.1 | 13.2 | 11.4 | 14.1 | 13.0 | 8,211
Omphalocele | 3,596,017 | 344 | 9.6 | 15.4 | 8.8 | 8.1 | 9.3 | 9.8 | 18.4 | 8,211
Gastroschisis | 3,596,017 | 565 | 15.7 | 65.3 | 38.5 | 12.7 | 6.9 | 5.5 | * | 8,211
Limb reduction defect | 3,596,017 | 405 | 11.3 | 16.8 | 14.1 | 11.9 | 9.9 | 8.5 | 11.6 | 8,211
Cleft lip with or without cleft palate | 3,596,017 | 1,856 | 51.7 | 74.4 | 56.2 | 49.4 | 48.4 | 50.4 | 57.3 | 8,211
Cleft palate alone | 3,596,017 | 796 | 22.2 | 18.9 | 23.7 | 20.5 | 23.1 | 21.4 | 26.6 | 8,211
Down syndrome | 3,596,017 | 1,855 | 51.7 | 26.7 | 32.5 | 24.5 | 31.7 | 92.4 | 321.9 | 8,211
Suspected chromosomal disorder | 3,596,017 | 1,620 | 45.2 | 45.6 | 46.3 | 34.4 | 35.7 | 57.2 | 133.0 | 8,211
Hypospadias^2^ | 3,596,017 | 1,839 | 51.3 | 34.4 | 48.2 | 51.0 | 52.0 | 56.0 | 56.6 | 8,211
Males only^3^ | 1,839,794 | 1,839 | 100.2 | 67.2 | 94.3 | 99.6 | 101.7 | 109.6 | 111.4 | 4,350

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 No response reported for selected characteristic.

2 Denominator includes both male and female births.

3 Denominator includes male births only.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

## Methods

Data shown in this report are based on 100% of the birth certificates registered in all states and D.C. to U.S. residents. More than 99% of births occurring in the United States are registered (9). Tables showing data by state also provide separate information for Puerto Rico, Guam, U.S. Virgin Islands, and Northern Marianas. These areas, however, are not included in totals for the United States. Data for American Samoa were not available for 2023.

The 2003 revision of the U.S. Standard Certificate of Live Birth allows the reporting of more than one race (multiple races) for each parent (10), according to the revised standards issued by the Office of Management and Budget (OMB) in 1997 (11). Starting in 2016, all 50 states, D.C., Puerto Rico, Guam, Northern Marianas, and U.S. Virgin Islands reported race data according to these standards that allow for the reporting of a minimum of five race categories, either by single race (reported alone) or in combination (more than one race or multiple races) (11). The race and Hispanic-origin groups shown in this report follow the 1997 standards and differ from the bridged-race categories shown in most previous reports that are based on data from 2015 and earlier (12). The categories are Hispanic; American Indian and Alaska Native, non-Hispanic single race (subsequently, American Indian and Alaska Native); Asian, non-Hispanic single race (subsequently, Asian); Black or African American, non-Hispanic single race (subsequently, Black); Native Hawaiian and Other Pacific Islander, non-Hispanic single race (subsequently, Native Hawaiian and Other Pacific Islander); and White, non-Hispanic single race (subsequently, White). Because single-race data are not available for the entire United States before 2016, race data for 2016–2023 only are shown in this report. For more information on differences between single- and bridged-race groups, see “Births: Final Data for 2016” (13).

Race and Hispanic origin are reported independently on the birth certificate, and reporting of Hispanic-origin ethnicity was not affected by the change to the 1997 OMB standards. Most tables in this report show data for the categories White, Black, and Hispanic. Selected tables also include data for the categories American Indian and Alaska Native, Asian, and Native Hawaiian and Other Pacific Islander. Data are also presented in some tables for specific Hispanic groups: Central and South American, Cuban, Dominican, Mexican, Puerto Rican, and other and unknown Hispanic (includes Hispanic origins not categorized, including Spaniard). Before 2018, data for the Dominican subgroup had been included in the category other and unknown Hispanic.

Trend tables included in the detailed tables for this report cover the 2010–2023 period; see List of Detailed Tables. Longer-term trends previously shown in this report series can be found in earlier reports (for example, “Births: Final Data for 2015”) (12).

In this report, the total number of births includes births to women up to age 64. In tables that include age of mother, the oldest age groups shown (40–54, 45–49, 45–54, or 50–54) include births to mothers up to age 64 (births to mothers 55–64 are included in the 50–54 age group).

For information on levels of incomplete reporting by state, see the 2023 User Guide (9). For information on the measurement of data items shown in this report and in the Technical Notes tables, imputation techniques used, computation of derived statistics, and definitions of terms, see the 2023 User Guide (9).

Birth and fertility rates for 2020 shown in this report have been revised and may differ from those published in “Births: Final Data for 2020” and elsewhere (14). Previously published birth and fertility rates for 2020 were based on postcensal population estimates derived from the 2010 census. The revised rates shown here are based on the blended base population estimates produced by the U.S. Census Bureau instead of the April 1, 2020, decennial population counts (Technical Notes).

## Demographic Characteristics (Tables 1–12)

### Births and birth rates

#### Number of births

In 2023, 3,596,017 births were registered in the United States, down 2% from 2022 (3,667,758). This follows essentially no change from 2021 to 2022, an increase of 1% from 2020 to 2021, and a decline of 4% from 2019 to 2020 (Table 1, Figure 1). From 2014 to 2019, the number of births had declined by an average 1% per year. Previously, the number of births declined by an average 2% per year from 2007 to 2013 and increased 1% in 2014 (12).

Figure 1 Live births and general fertility rate: United States, 1970–2023

NOTE: Rate for 2020 has been revised and differs from that published in “Births: Final Data for 2020.”

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 1 is a line graph showing live births and the general fertility rate in the United States, 1970–2023.

Table 1 Births and birth rates: United States, 2010–2023, and by race and Hispanic origin of mother: United States, 2016–2023

[Birth rates are births per 1,000 population in specified group. Fertility rates are births per 1,000 females ages 15–44 in specified group. Populations based on counts enumerated as of April 1 for 2010 and estimated as of April 1 for 2020 and July 1 for all other years]

Race and Hispanic origin and year | Number of births | Birth rate | Fertility rate
All races and origins^1^
2023 | 3,596,017 | 10.7 | 54.5
2022 | 3,667,758 | 11.0 | 56.0
2021 | 3,664,292 | 11.0 | 56.3
2020 | 3,613,647 | 10.9 | 55.7
2019 | 3,747,540 | 11.4 | 58.3
2018 | 3,791,712 | 11.6 | 59.1
2017 | 3,855,500 | 11.8 | 60.3
2016 | 3,945,875 | 12.2 | 62.0
2015 | 3,978,497 | 12.4 | 62.5
2014 | 3,988,076 | 12.5 | 62.9
2013 | 3,932,181 | 12.4 | 62.5
2012 | 3,952,841 | 12.6 | 63.0
2011 | 3,953,590 | 12.7 | 63.2
2010 | 3,999,386 | 13.0 | 64.1
Non-Hispanic, single race^2^
American Indian and Alaska Native:
2023 | 24,571 | 10.3 | 48.0
2022 | 25,721 | 10.8 | 50.6
2021 | 26,124 | 10.8 | 50.8
2020 | 26,813 | 11.1 | 52.6
2019 | 28,450 | 11.9 | 56.2
2018 | 29,092 | 12.2 | 57.7
2017 | 29,957 | 12.6 | 59.5
2016 | 31,452 | 13.3 | 62.7
Asian:
2023 | 215,738 | 10.7 | 47.8
2022 | 218,994 | 11.1 | 49.4
2021 | 213,813 | 11.2 | 49.6
2020 | 219,068 | 11.6 | 50.4
2019 | 238,769 | 13.0 | 55.3
2018 | 240,798 | 13.2 | 55.6
2017 | 249,250 | 13.8 | 58.0
2016 | 254,471 | 14.6 | 61.1
Black:
2023 | 491,494 | 11.7 | 53.7
2022 | 511,439 | 12.3 | 56.1
2021 | 517,889 | 12.5 | 57.4
2020 | 529,811 | 12.8 | 58.9
2019 | 548,075 | 13.4 | 61.4
2018 | 552,029 | 13.6 | 62.0
2017 | 560,715 | 13.9 | 63.1
2016 | 558,622 | 14.0 | 63.3
Native Hawaiian and Pacific Islander:
2023 | 10,115 | 16.1 | 73.2
2022 | 10,122 | 16.5 | 74.8
2021 | 9,531 | 15.8 | 71.5
2020 | 9,626 | 16.1 | 72.5
2019 | 9,770 | 17.0 | 74.9
2018 | 9,476 | 16.6 | 73.0
2017 | 9,426 | 16.7 | 72.8
2016 | 9,342 | 16.8 | 72.9
White:
2023 | 1,787,051 | 9.3 | 51.7
2022 | 1,840,739 | 9.5 | 53.1
2021 | 1,887,656 | 9.7 | 54.4
2020 | 1,843,432 | 9.4 | 53.0
2019 | 1,915,912 | 9.8 | 55.3
2018 | 1,956,413 | 10.0 | 56.3
2017 | 1,992,461 | 10.2 | 57.2
2016 | 2,056,332 | 10.5 | 58.8
Hispanic^3^
2023 | 945,200 | 14.5 | 64.7
2022 | 937,421 | 14.7 | 65.7
2021 | 885,916 | 14.1 | 63.4
2020 | 866,713 | 14.0 | 62.9
2019 | 886,467 | 14.6 | 65.3
2018 | 886,210 | 14.8 | 65.9
2017 | 898,764 | 15.2 | 67.6
2016 | 918,447 | 16.0 | 70.6

1 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

2 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

NOTE: Rates for 2020 have been revised and may differ from those published in “Births: Final Data for 2020”; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 2 Birth rates, by age of mother: United States, 2010–2023, and by age and race and Hispanic origin of mother: United States, 2016–2023

[Total fertility rates are sums of birth rates for 5-year age groups multiplied by 5. Birth rates are births per 1,000 women in specified group. Populations based on counts enumerated as of April 1 for 2010 and estimated as of April 1 for 2020 and July 1 for all other years]

Race and Hispanic origin of mother and year | Total fertility rate | Age of mother
Race and Hispanic origin of mother and year | Total fertility rate | 10–14 | 15–19 | | | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49^1^
Race and Hispanic origin of mother and year | Total fertility rate | 10–14 | Total | 15–17 | 18–19 | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49^1^
All races and origins^2^
2023 | 1,621.0 | 0.2 | 13.1 | 5.5 | 24.6 | 57.7 | 91.0 | 94.3 | 54.3 | 12.5 | 1.1
2022 | 1,656.5 | 0.2 | 13.6 | 5.6 | 25.8 | 57.5 | 93.5 | 97.5 | 55.3 | 12.6 | 1.1
2021 | 1,664.0 | 0.2 | 13.9 | 5.6 | 26.6 | 61.5 | 93.0 | 97.6 | 53.7 | 12.0 | 0.9
2020 | 1,641.5 | 0.2 | 15.0 | 6.1 | 28.2 | 63.3 | 90.9 | 94.9 | 51.3 | 11.8 | 0.9
2019 | 1,706.0 | 0.2 | 16.7 | 6.7 | 31.1 | 66.6 | 93.7 | 98.3 | 52.8 | 12.0 | 0.9
2018 | 1,729.5 | 0.2 | 17.4 | 7.2 | 32.3 | 68.0 | 95.3 | 99.7 | 52.6 | 11.8 | 0.9
2017 | 1,765.5 | 0.2 | 18.8 | 7.9 | 35.1 | 71.0 | 98.0 | 100.3 | 52.3 | 11.6 | 0.9
2016 | 1,820.5 | 0.2 | 20.3 | 8.8 | 37.5 | 73.8 | 102.1 | 102.7 | 52.7 | 11.4 | 0.9
2015 | 1,843.5 | 0.2 | 22.3 | 9.9 | 40.7 | 76.8 | 104.3 | 101.5 | 51.8 | 11.0 | 0.8
2014 | 1,862.5 | 0.3 | 24.2 | 10.9 | 43.8 | 79.0 | 105.8 | 100.8 | 51.0 | 10.6 | 0.8
2013 | 1,857.5 | 0.3 | 26.5 | 12.3 | 47.1 | 80.7 | 105.5 | 98.0 | 49.3 | 10.4 | 0.8
2012 | 1,880.5 | 0.4 | 29.4 | 14.1 | 51.4 | 83.1 | 106.5 | 97.3 | 48.3 | 10.4 | 0.7
2011 | 1,894.5 | 0.4 | 31.3 | 15.4 | 54.1 | 85.3 | 107.2 | 96.5 | 47.2 | 10.3 | 0.7
2010 | 1,931.0 | 0.4 | 34.2 | 17.3 | 58.2 | 90.0 | 108.3 | 96.5 | 45.9 | 10.2 | 0.7
Non-Hispanic, single race^3^ American Indian and Alaska Native:
2023 | 1,411.0 | 0.3 | 20.9 | 9.4 | 38.6 | 73.2 | 78.7 | 64.0 | 36.1 | 8.4 | 0.6
2022 | 1,470.0 | 0.4 | 22.5 | 9.5 | 42.5 | 74.3 | 82.8 | 68.1 | 36.3 | 9.1 | 0.5
2021 | 1,477.0 | 0.3 | 24.2 | 11.3 | 44.1 | 78.7 | 81.9 | 66.1 | 36.2 | 7.5 | 0.5
2020 | 1,520.5 | 0.4 | 25.2 | 11.0 | 46.3 | 82.2 | 83.2 | 68.8 | 35.9 | 8.1 | 0.3
2019 | 1,611.5 | 0.3 | 29.2 | 13.5 | 51.8 | 86.7 | 89.1 | 72.0 | 36.6 | 8.0 | 0.4
2018 | 1,650.5 | 0.2 | 29.7 | 13.5 | 52.9 | 87.7 | 94.4 | 73.2 | 36.1 | 8.3 | 0.5
2017 | 1,702.0 | 0.5 | 32.9 | 15.7 | 58.1 | 93.6 | 96.4 | 72.1 | 36.3 | 8.2 | 0.4
2016 | 1,794.5 | 0.5 | 35.1 | 16.8 | 62.6 | 97.2 | 103.4 | 77.1 | 37.1 | 8.2 | 0.3
Asian:
2023 | 1,309.0 | * | 1.8 | 0.6 | 3.4 | 15.6 | 56.2 | 101.3 | 68.4 | 16.7 | 1.8
2022 | 1,353.0 | * | 1.9 | 0.7 | 3.7 | 16.4 | 58.6 | 104.0 | 70.9 | 17.0 | 1.8
2021 | 1,351.5 | * | 2.0 | 0.7 | 3.8 | 17.7 | 60.4 | 105.0 | 67.9 | 15.8 | 1.5
2020 | 1,379.0 | * | 2.2 | 0.8 | 4.3 | 20.4 | 63.9 | 105.5 | 66.6 | 15.5 | 1.7
2019 | 1,511.0 | * | 2.7 | 0.9 | 5.2 | 23.1 | 71.4 | 115.6 | 71.0 | 16.5 | 1.9
2018 | 1,525.0 | * | 2.8 | 1.0 | 5.4 | 24.1 | 73.0 | 116.5 | 70.7 | 16.1 | 1.8
2017 | 1,597.0 | * | 3.3 | 1.1 | 6.5 | 26.6 | 79.6 | 120.1 | 71.5 | 16.5 | 1.8
2016 | 1,690.5 | * | 3.9 | 1.4 | 7.5 | 28.9 | 87.0 | 127.4 | 72.8 | 16.4 | 1.7
Black:
2023 | 1,581.0 | 0.3 | 19.3 | 8.9 | 35.5 | 69.7 | 85.3 | 76.5 | 49.7 | 13.9 | 1.5
2022 | 1,639.0 | 0.3 | 20.3 | 9.0 | 37.7 | 71.1 | 90.7 | 79.8 | 50.4 | 13.8 | 1.4
2021 | 1,675.0 | 0.3 | 21.8 | 9.3 | 40.6 | 79.1 | 91.9 | 79.7 | 48.2 | 12.8 | 1.2
2020 | 1,713.5 | 0.3 | 23.7 | 10.5 | 42.7 | 84.0 | 93.4 | 80.4 | 47.1 | 12.7 | 1.1
2019 | 1,775.5 | 0.4 | 25.8 | 11.1 | 46.4 | 88.3 | 96.4 | 82.9 | 47.6 | 12.6 | 1.1
2018 | 1,792.0 | 0.4 | 26.3 | 11.9 | 46.9 | 90.0 | 97.1 | 84.1 | 47.1 | 12.3 | 1.1
2017 | 1,824.5 | 0.4 | 27.5 | 12.5 | 49.8 | 94.2 | 99.5 | 84.5 | 46.1 | 11.7 | 1.0
2016 | 1,832.5 | 0.5 | 29.3 | 13.7 | 52.5 | 95.8 | 100.8 | 83.0 | 45.0 | 11.1 | 1.0
Native Hawaiian and Pacific Islander:
2023 | 2,218.0 | * | 21.2 | 7.5 | 41.4 | 115.3 | 137.3 | 95.8 | 56.7 | 15.8 | 1.4
2022 | 2,237.5 | * | 20.5 | 7.3 | 40.7 | 123.0 | 132.4 | 98.0 | 56.6 | 15.5 | 1.3
2021 | 2,131.0 | * | 21.9 | 7.3 | 44.6 | 116.1 | 124.7 | 95.8 | 51.2 | 15.0 | 1.3
2020 | 2,134.5 | * | 22.2 | 7.7 | 44.5 | 120.5 | 125.3 | 91.6 | 51.5 | 14.6 | *
2019 | 2,178.0 | * | 26.2 | 7.7 | 53.8 | 121.4 | 123.5 | 95.3 | 54.1 | 14.2 | *
2018 | 2,106.5 | * | 26.5 | 8.2 | 53.7 | 118.5 | 118.9 | 91.9 | 49.2 | 15.4 | *
2017 | 2,085.5 | * | 25.5 | 8.7 | 50.6 | 113.3 | 115.7 | 94.0 | 54.6 | 13.1 | *
2016 | 2,076.5 | * | 28.6 | 11.0 | 55.3 | 109.5 | 115.5 | 96.0 | 49.9 | 14.7 | *
White:
2023 | 1,532.5 | 0.1 | 8.4 | 2.9 | 16.7 | 48.3 | 89.2 | 97.1 | 51.9 | 10.6 | 0.9
2022 | 1,568.0 | 0.1 | 9.1 | 3.1 | 17.9 | 48.3 | 91.1 | 100.4 | 53.0 | 10.7 | 0.9
2021 | 1,598.5 | 0.1 | 9.4 | 3.2 | 18.7 | 52.0 | 91.8 | 102.3 | 52.8 | 10.5 | 0.8
2020 | 1,551.0 | 0.1 | 10.1 | 3.4 | 19.9 | 53.1 | 88.2 | 98.2 | 49.7 | 10.1 | 0.7
2019 | 1,610.5 | 0.1 | 11.4 | 3.8 | 22.3 | 56.1 | 90.8 | 101.5 | 51.1 | 10.3 | 0.8
2018 | 1,640.0 | 0.1 | 12.1 | 4.1 | 23.6 | 57.8 | 92.9 | 103.1 | 51.1 | 10.2 | 0.7
2017 | 1,666.5 | 0.1 | 13.2 | 4.6 | 26.0 | 59.8 | 95.3 | 103.7 | 50.6 | 9.9 | 0.7
2016 | 1,719.0 | 0.1 | 14.3 | 5.2 | 27.7 | 62.4 | 99.3 | 106.2 | 51.1 | 9.7 | 0.7
Hispanic^4^
2023 | 1,946.0 | 0.3 | 20.8 | 9.3 | 39.0 | 81.1 | 111.2 | 100.3 | 59.0 | 15.4 | 1.1
2022 | 1,969.5 | 0.3 | 21.3 | 9.3 | 40.1 | 79.2 | 113.8 | 103.1 | 59.5 | 15.5 | 1.2
2021 | 1,899.0 | 0.3 | 21.1 | 9.3 | 39.8 | 82.3 | 108.3 | 97.5 | 54.9 | 14.4 | 1.0
2020 | 1,879.5 | 0.3 | 23.0 | 10.3 | 42.5 | 83.8 | 105.8 | 94.4 | 53.4 | 14.2 | 1.0
2019 | 1,940.0 | 0.3 | 25.3 | 11.5 | 46.2 | 88.0 | 108.0 | 96.3 | 54.6 | 14.5 | 1.0
2018 | 1,959.0 | 0.3 | 26.7 | 12.4 | 48.5 | 89.3 | 108.9 | 96.6 | 54.5 | 14.5 | 1.0
2017 | 2,006.5 | 0.3 | 28.9 | 13.6 | 52.7 | 93.8 | 111.8 | 96.4 | 54.6 | 14.5 | 1.0
2016 | 2,092.5 | 0.4 | 31.9 | 15.6 | 57.3 | 98.4 | 117.4 | 99.2 | 55.8 | 14.5 | 0.9

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Birth rates computed by relating births to women age 45 and older to women ages 45–49; see Technical Notes in this report.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race females, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic females are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

NOTE: Rates for 2020 have been revised and may differ from those published in ‘‘Births: Final Data for 2020”; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 3 Births, by age of mother, live-birth order, and race and Hispanic origin of mother: United States, 2023

[Live-birth order is number of children born alive to mother]

Race and Hispanic origin of mother and live-birth order | All ages | Younger than 15 | 15–19 | | | | | | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49 | 50–54
Race and Hispanic origin of mother and live-birth order | All ages | Younger than 15 | Total | 15 | 16 | 17 | 18 | 19 | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49 | 50–54
All races and origins^1^
Total | 3,596,017 | 1,766 | 140,977 | 4,534 | 10,714 | 20,466 | 38,362 | 66,901 | 616,970 | 986,567 | 1,098,052 | 604,631 | 136,333 | 9,504 | 1,217
1st child | 1,406,183 | 1,723 | 121,216 | 4,385 | 10,185 | 18,691 | 33,220 | 54,735 | 352,886 | 400,918 | 353,122 | 144,307 | 29,001 | 2,648 | 362
2nd child | 1,126,450 | 36 | 17,447 | 130 | 477 | 1,641 | 4,634 | 10,565 | 185,092 | 319,606 | 365,152 | 198,482 | 37,855 | 2,454 | 326
3rd child | 589,447 | * | 1,874 | * | 29 | 100 | 407 | 1,329 | 58,911 | 164,289 | 207,896 | 127,468 | 27,282 | 1,527 | 198
4th child | 262,793 | * | 165 | * | * | * | 33 | 126 | 14,517 | 65,310 | 97,022 | 67,230 | 17,419 | 1,007 | 122
5th child | 108,652 | * | 24 | * | * | * | * | 22 | 3,076 | 22,560 | 40,540 | 31,798 | 9,917 | 655 | 82
6th child | 47,180 | * | * | * | * | * | * | * | 621 | 7,437 | 17,556 | 15,615 | 5,492 | 406 | 53
7th child | 21,661 | * | * | * | * | * | * | * | 149 | 2,384 | 7,842 | 7,957 | 3,078 | 222 | 28
8th child or higher order | 23,870 | * | * | * | * | * | * | * | 195 | 1,407 | 5,979 | 9,921 | 5,783 | 541 | 36
Not stated | 9,781 | * | 242 | * | 20 | 30 | 63 | 120 | 1,523 | 2,656 | 2,943 | 1,853 | 506 | 44 | 10
Non-Hispanic, single race^2^
American Indian and Alaska Native | 24,571 | 23 | 1,841 | 77 | 155 | 271 | 510 | 828 | 6,285 | 6,843 | 5,970 | 2,942 | 630 | 33 | *
1st child | 7,930 | 23 | 1,534 | 74 | 148 | 241 | 425 | 646 | 3,170 | 1,834 | 954 | 346 | 64 | * | *
2nd child | 6,417 | * | 266 | * | * | 27 | 73 | 157 | 1,999 | 2,069 | 1,435 | 546 | 97 | * | *
3rd child | 4,454 | * | 30 | * | * | * | * | 21 | 808 | 1,544 | 1,374 | 574 | 118 | * | *
4th child | 2,617 | * | * | * | * | * | * | * | 217 | 812 | 944 | 536 | 101 | * | *
5th child | 1,435 | * | * | * | * | * | * | * | 42 | 339 | 583 | 372 | 90 | * | *
6th child | 789 | * | * | * | * | * | * | * | 13 | 137 | 344 | 236 | 54 | * | *
7th child | 379 | * | * | * | * | * | * | * | * | 41 | 155 | 146 | 34 | * | *
8th child or higher order | 389 | * | * | * | * | * | * | * | * | 21 | 138 | 160 | 68 | * | *
Not stated | 161 | * | * | * | * | * | * | * | 33 | 46 | 43 | 26 | * | * | *
Asian | 215,738 | * | 925 | 17 | 56 | 117 | 226 | 509 | 9,420 | 40,837 | 88,489 | 60,802 | 13,951 | 1,097 | 210
1st child | 99,574 | * | 816 | 17 | 53 | 110 | 193 | 443 | 6,368 | 24,624 | 43,444 | 19,754 | 4,068 | 420 | 73
2nd child | 77,710 | * | 93 | * | * | * | 29 | 55 | 2,301 | 11,061 | 31,945 | 26,589 | 5,327 | 330 | 64
3rd child | 25,032 | * | 13 | * | * | * | * | * | 535 | 3,444 | 8,722 | 9,422 | 2,686 | 178 | 32
4th child | 8,184 | * | * | * | * | * | * | * | 150 | 1,079 | 2,746 | 3,046 | 1,052 | 88 | 22
5th child | 2,875 | * | * | * | * | * | * | * | 35 | 363 | 908 | 1,107 | 416 | 39 | *
6th child | 1,053 | * | * | * | * | * | * | * | * | 121 | 318 | 399 | 187 | 15 | *
7th child | 411 | * | * | * | * | * | * | * | * | 30 | 127 | 159 | 79 | * | *
8th child or higher order | 367 | * | * | * | * | * | * | * | * | 15 | 76 | 161 | 96 | 15 | *
Not stated | 532 | * | * | * | * | * | * | * | 17 | 100 | 203 | 165 | 40 | * | *
Black | 491,494 | 486 | 28,414 | 1,164 | 2,416 | 4,431 | 7,672 | 12,731 | 103,077 | 131,705 | 131,500 | 74,492 | 19,925 | 1,581 | 314
1st child | 172,039 | 476 | 24,129 | 1,122 | 2,296 | 4,004 | 6,569 | 10,138 | 56,800 | 43,267 | 29,759 | 13,579 | 3,549 | 379 | 101
2nd child | 137,978 | 10 | 3,736 | 38 | 111 | 385 | 976 | 2,226 | 30,335 | 41,302 | 37,784 | 19,546 | 4,753 | 426 | 86
3rd child | 88,077 | * | 442 | * | * | 32 | 102 | 300 | 11,069 | 25,445 | 29,440 | 17,162 | 4,218 | 260 | 41
4th child | 47,610 | * | 55 | * | * | * | 10 | 43 | 3,519 | 12,423 | 17,266 | 11,099 | 3,032 | 197 | 19
5th child | 22,706 | * | * | * | * | * | * | * | 839 | 5,471 | 8,636 | 5,881 | 1,749 | 103 | 21
6th child | 10,887 | * | * | * | * | * | * | * | 192 | 2,159 | 4,286 | 3,132 | 1,026 | 77 | 15
7th child | 5,449 | * | * | * | * | * | * | * | 61 | 818 | 2,186 | 1,721 | 604 | 47 | 12
8th child or higher order | 5,464 | * | * | * | * | * | * | * | 40 | 475 | 1,792 | 2,139 | 917 | 83 | 16
Not stated | 1,284 | * | 44 | * | * | * | 13 | 18 | 222 | 345 | 351 | 233 | 77 | * | *
Native Hawaiian and Pacific Islander | 10,115 | * | 459 | 10 | 23 | 64 | 123 | 239 | 2,424 | 3,031 | 2,409 | 1,401 | 364 | 24 | *
1st child | 2,876 | * | 376 | 10 | 22 | 58 | 100 | 186 | 1,136 | 750 | 420 | 153 | 35 | * | *
2nd child | 2,472 | * | 69 | * | * | * | 21 | 43 | 757 | 802 | 530 | 258 | 54 | * | *
3rd child | 1,844 | * | * | * | * | * | * | * | 369 | 690 | 473 | 246 | 55 | * | *
4th child | 1,242 | * | * | * | * | * | * | * | 102 | 451 | 377 | 239 | 68 | * | *
5th child | 732 | * | * | * | * | * | * | * | 22 | 189 | 266 | 211 | 40 | * | *
6th child | 403 | * | * | * | * | * | * | * | * | 65 | 159 | 129 | 39 | * | *
7th child | 225 | * | * | * | * | * | * | * | * | 34 | 96 | 69 | 20 | * | *
8th child or higher order | 231 | * | * | * | * | * | * | * | * | 17 | 72 | 88 | 50 | * | *
Not stated | 90 | * | * | * | * | * | * | * | 24 | 33 | 16 | * | * | * | *
White | 1,787,051 | 351 | 44,922 | 1,029 | 2,700 | 5,500 | 11,970 | 23,723 | 263,760 | 500,910 | 595,741 | 314,198 | 62,607 | 4,134 | 428
1st child | 720,316 | 341 | 39,037 | 996 | 2,590 | 5,095 | 10,508 | 19,848 | 154,644 | 222,606 | 206,692 | 80,594 | 15,042 | 1,241 | 119
2nd child | 585,538 | * | 5,205 | 28 | 98 | 382 | 1,321 | 3,376 | 78,096 | 162,650 | 209,427 | 110,114 | 18,779 | 1,135 | 123
3rd child | 280,410 | * | 550 | * | * | 15 | 109 | 418 | 23,776 | 74,157 | 104,904 | 64,637 | 11,692 | 616 | 78
4th child | 112,465 | * | 33 | * | * | * | * | 25 | 5,229 | 27,458 | 43,244 | 29,624 | 6,528 | 310 | 39
5th child | 43,272 | * | * | * | * | * | * | * | 1,044 | 8,865 | 16,830 | 12,770 | 3,497 | 234 | 26
6th child | 19,039 | * | * | * | * | * | * | * | 197 | 2,700 | 7,357 | 6,560 | 2,061 | 144 | 20
7th child | 9,136 | * | * | * | * | * | * | * | 39 | 773 | 3,308 | 3,614 | 1,309 | 88 | *
8th child or higher order | 12,271 | * | * | * | * | * | * | * | 81 | 465 | 2,513 | 5,388 | 3,460 | 350 | 13
Not stated | 4,604 | * | 90 | * | * | * | 24 | 49 | 654 | 1,236 | 1,466 | 897 | 239 | 16 | *
Hispanic^3^
Total | 945,200 | 800 | 57,914 | 2,021 | 4,788 | 9,071 | 16,108 | 25,926 | 207,702 | 270,317 | 240,489 | 131,623 | 34,043 | 2,159 | 153
1st child | 353,899 | 782 | 49,713 | 1,955 | 4,525 | 8,246 | 13,905 | 21,082 | 117,211 | 95,187 | 60,766 | 24,613 | 5,111 | 469 | 47
2nd child | 280,851 | 14 | 7,302 | 56 | 236 | 769 | 2,001 | 4,240 | 64,391 | 91,589 | 74,048 | 35,509 | 7,526 | 443 | 29
3rd child | 170,848 | * | 755 | * | 16 | 46 | 172 | 516 | 19,910 | 53,287 | 56,935 | 31,934 | 7,599 | 394 | 32
4th child | 81,652 | * | 66 | * | * | * | 12 | 50 | 4,642 | 20,560 | 29,230 | 20,694 | 6,079 | 356 | 24
5th child | 33,629 | * | 12 | * | * | * | * | 11 | 938 | 6,387 | 11,825 | 10,425 | 3,809 | 224 | *
6th child | 13,183 | * | * | * | * | * | * | * | 176 | 1,926 | 4,434 | 4,593 | 1,917 | 130 | *
7th child | 5,257 | * | * | * | * | * | * | * | 33 | 578 | 1,654 | 1,993 | 934 | 62 | *
8th child or higher order | 4,293 | * | * | * | * | * | * | * | 62 | 349 | 1,172 | 1,629 | 999 | 76 | *
Not stated | 1,588 | * | 62 | * | * | * | 16 | 26 | 339 | 454 | 425 | 233 | 69 | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

2 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic females are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 4 Births, by age of mother, live-birth order, and Hispanic origin of mother: United States, 2023

[Live-birth order is number of children born alive to mother. Includes births with stated origin of mother only]

Origin of mother and live-birth order | All ages | Younger than 15 | 15–19 | | | | | | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49 | 50–54
Origin of mother and live-birth order | All ages | Younger than 15 | Total | 15 | 16 | 17 | 18 | 19 | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49 | 50–54
Hispanic
Total | 945,200 | 800 | 57,914 | 2,021 | 4,788 | 9,071 | 16,108 | 25,926 | 207,702 | 270,317 | 240,489 | 131,623 | 34,043 | 2,159 | 153
1st child | 353,899 | 782 | 49,713 | 1,955 | 4,525 | 8,246 | 13,905 | 21,082 | 117,211 | 95,187 | 60,766 | 24,613 | 5,111 | 469 | 47
2nd child | 280,851 | 14 | 7,302 | 56 | 236 | 769 | 2,001 | 4,240 | 64,391 | 91,589 | 74,048 | 35,509 | 7,526 | 443 | 29
3rd child | 170,848 | * | 755 | * | 16 | 46 | 172 | 516 | 19,910 | 53,287 | 56,935 | 31,934 | 7,599 | 394 | 32
4th child | 81,652 | * | 66 | * | * | * | 12 | 50 | 4,642 | 20,560 | 29,230 | 20,694 | 6,079 | 356 | 24
5th child | 33,629 | * | 12 | * | * | * | * | 11 | 938 | 6,387 | 11,825 | 10,425 | 3,809 | 224 | *
6th child | 13,183 | * | * | * | * | * | * | * | 176 | 1,926 | 4,434 | 4,593 | 1,917 | 130 | *
7th child | 5,257 | * | * | * | * | * | * | * | 33 | 578 | 1,654 | 1,993 | 934 | 62 | *
8th child or higher order | 4,293 | * | * | * | * | * | * | * | 62 | 349 | 1,172 | 1,629 | 999 | 76 | *
Not stated | 1,588 | * | 62 | * | * | * | 16 | 26 | 339 | 454 | 425 | 233 | 69 | * | *
Central and South American | 208,618 | 304 | 14,324 | 544 | 1,257 | 2,329 | 4,176 | 6,018 | 42,377 | 56,021 | 52,706 | 32,976 | 9,274 | 601 | 35
1st child | 77,674 | 296 | 12,145 | 520 | 1,183 | 2,104 | 3,540 | 4,798 | 23,277 | 19,616 | 14,095 | 6,607 | 1,472 | 151 | 15
2nd child | 64,973 | * | 1,960 | 22 | 63 | 212 | 582 | 1,081 | 13,883 | 19,950 | 17,211 | 9,497 | 2,329 | 131 | *
3rd child | 38,438 | * | 186 | * | * | 12 | 45 | 123 | 4,155 | 11,102 | 12,485 | 8,189 | 2,206 | 108 | *
4th child | 16,807 | * | 10 | * | * | * | * | * | 814 | 3,822 | 5,703 | 4,804 | 1,554 | 92 | *
5th child | 6,603 | * | * | * | * | * | * | * | 136 | 1,081 | 2,116 | 2,298 | 911 | 57 | *
6th child | 2,304 | * | * | * | * | * | * | * | 19 | 261 | 671 | 906 | 415 | 31 | *
7th child | 888 | * | * | * | * | * | * | * | * | 54 | 224 | 388 | 206 | 13 | *
8th child or higher order | 622 | * | * | * | * | * | * | * | 17 | 41 | 132 | 244 | 171 | 16 | *
Not stated | 309 | * | 17 | * | * | * | * | * | 74 | 94 | 69 | 43 | 10 | * | *
Cuban | 30,001 | * | 639 | 12 | 27 | 66 | 154 | 380 | 4,816 | 8,314 | 9,659 | 5,447 | 1,042 | 73 | *
1st child | 14,558 | * | 588 | 11 | 27 | 62 | 143 | 345 | 3,504 | 4,604 | 3,903 | 1,627 | 297 | 27 | *
2nd child | 10,510 | * | 48 | * | * | * | 10 | 34 | 1,070 | 2,733 | 3,889 | 2,372 | 373 | 25 | *
3rd child | 3,438 | * | * | * | * | * | * | * | 186 | 702 | 1,312 | 989 | 234 | 13 | *
4th child | 958 | * | * | * | * | * | * | * | 37 | 185 | 350 | 303 | 75 | * | *
5th child | 273 | * | * | * | * | * | * | * | * | 49 | 111 | 73 | 34 | * | *
6th child | 116 | * | * | * | * | * | * | * | * | 19 | 36 | 45 | 12 | * | *
7th child | 43 | * | * | * | * | * | * | * | * | * | 16 | 11 | 10 | * | *
8th child or higher order | 53 | * | * | * | * | * | * | * | * | * | 22 | 20 | * | * | *
Not stated | 52 | * | * | * | * | * | * | * | * | 14 | 20 | * | * | * | *
Dominican | 33,575 | 12 | 1,198 | 42 | 83 | 165 | 323 | 585 | 6,116 | 9,301 | 10,013 | 5,388 | 1,434 | 99 | 14
1st child | 13,160 | 10 | * | 41 | 72 | 153 | 291 | 497 | 4,044 | 3,866 | 2,795 | 1,097 | 262 | 24 | *
2nd child | 11,319 | * | * | * | 10 | 12 | 31 | 83 | 1,639 | 3,437 | 3,765 | 1,855 | 452 | 31 | *
3rd child | 6,034 | * | * | * | * | * | * | * | 349 | 1,477 | 2,304 | 1,474 | 404 | 18 | *
4th child | 2,109 | * | * | * | * | * | * | * | 61 | 380 | 826 | 618 | 205 | 18 | *
5th child | 614 | * | * | * | * | * | * | * | 15 | 94 | 199 | 232 | 67 | * | *
6th child | 174 | * | * | * | * | * | * | * | * | 24 | 66 | 61 | 22 | * | *
7th child | 59 | * | * | * | * | * | * | * | * | * | 24 | 20 | * | * | *
8th child or higher order | 47 | * | * | * | * | * | * | * | * | * | 12 | 19 | 11 | * | *
Not stated | 59 | * | * | * | * | * | * | * | * | 14 | 22 | 12 | * | * | *
Mexican | 508,127 | 356 | 31,865 | 1,052 | 2,616 | 4,996 | 8,804 | 14,397 | 117,437 | 149,457 | 125,796 | 65,363 | 16,768 | 1,030 | 55
1st child | 184,634 | 352 | 27,372 | 1,024 | 2,473 | 4,533 | 7,599 | 11,743 | 65,719 | 50,377 | 28,281 | 10,374 | 1,985 | 164 | 10
2nd child | 144,491 | * | 3,977 | 22 | 131 | 428 | 1,089 | 2,307 | 36,467 | 49,726 | 36,053 | 15,134 | 2,941 | 176 | 13
3rd child | 94,392 | * | 431 | * | * | 27 | 100 | 292 | 11,457 | 30,874 | 31,587 | 16,214 | 3,619 | 199 | 11
4th child | 48,714 | * | 45 | * | * | * | * | 36 | 2,842 | 12,475 | 17,670 | 12,033 | 3,456 | 183 | 10
5th child | 20,643 | * | * | * | * | * | * | * | 601 | 3,916 | 7,370 | 6,337 | 2,278 | 132 | *
6th child | 8,403 | * | * | * | * | * | * | * | 119 | 1,243 | 2,819 | 2,911 | 1,223 | 82 | *
7th child | 3,306 | * | * | * | * | * | * | * | 20 | 393 | 1,053 | 1,217 | 579 | 44 | *
8th child or higher order | 2,719 | * | * | * | * | * | * | * | 32 | 212 | 751 | 1,027 | 648 | 47 | *
Not stated | 825 | * | 34 | * | * | * | * | 14 | 180 | 241 | 212 | 116 | 39 | * | *
Puerto Rican | 66,203 | 30 | 3,800 | 135 | 277 | 575 | 1,047 | 1,766 | 15,415 | 19,476 | 16,884 | 8,477 | 1,966 | 148 | *
1st child | 25,970 | 30 | 3,311 | 130 | 265 | 530 | 916 | 1,470 | 8,780 | 6,941 | 4,627 | 1,825 | 400 | 56 | *
2nd child | 19,930 | * | 435 | * | 11 | 42 | 116 | 261 | 4,609 | 6,381 | 5,359 | 2,588 | 535 | 23 | *
3rd child | 11,196 | * | 41 | * | * | * | 11 | 27 | 1,514 | 3,747 | 3,610 | 1,855 | 403 | 22 | *
4th child | 5,133 | * | * | * | * | * | * | * | 371 | 1,540 | 1,824 | 1,107 | 261 | 24 | *
5th child | 2,172 | * | * | * | * | * | * | * | 73 | 553 | 821 | 544 | 169 | * | *
6th child | 832 | * | * | * | * | * | * | * | 14 | 161 | 323 | 246 | 82 | * | *
7th child | 413 | * | * | * | * | * | * | * | * | 57 | 148 | 147 | 49 | * | *
8th child or higher order | 356 | * | * | * | * | * | * | * | * | 41 | 107 | 135 | 63 | * | *
Not stated | 201 | * | * | * | * | * | * | * | 41 | 55 | 65 | 30 | * | * | *
Other and unknown Hispanic | 98,676 | 94 | 6,088 | 236 | 528 | 940 | 1,604 | 2,780 | 21,541 | 27,748 | 25,431 | 13,972 | 3,559 | 208 | 35
1st child | 37,903 | 90 | 5,243 | 229 | 505 | 864 | 1,416 | 2,229 | 11,887 | 9,783 | 7,065 | 3,083 | 695 | 47 | 10
2nd child | 29,628 | * | 745 | * | 21 | 71 | 173 | 474 | 6,723 | 9,362 | 7,771 | 4,063 | 896 | 57 | *
3rd child | 17,350 | * | 91 | * | * | * | 15 | 69 | 2,249 | 5,385 | 5,637 | 3,213 | 733 | 34 | *
4th child | 7,931 | * | * | * | * | * | * | * | 517 | 2,158 | 2,857 | 1,829 | 528 | 33 | *
5th child | 3,324 | * | * | * | * | * | * | * | 109 | 694 | 1,208 | 941 | 350 | 18 | *
6th child | 1,354 | * | * | * | * | * | * | * | 20 | 218 | 519 | 424 | 163 | 10 | *
7th child | 548 | * | * | * | * | * | * | * | * | 63 | 189 | 210 | 81 | * | *
8th child or higher order | 496 | * | * | * | * | * | * | * | * | 49 | 148 | 184 | 101 | * | *
Not stated | 142 | * | * | * | * | * | * | * | 29 | 36 | 37 | 25 | 12 | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

NOTES: In this table, Hispanic females are classified only by place of origin; non-Hispanic females are not shown. Other and unknown Hispanic includes origins not otherwise classified, including Spaniard. See Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 5 Birth rates, by age of mother, live-birth order, and race and Hispanic origin of mother: United States, 2023

[Rates are births per 1,000 females in specified age and race and Hispanic origin group. Fertility rate computed by relating total births, regardless of age of mother, to females ages 15–44. Populations estimated as of July 1. Live-birth order is number of children born alive to mother. Data for live-birth order not stated are distributed]

Race and Hispanic origin of mother and live-birth order | Fertility rate | Age of mother
Race and Hispanic origin of mother and live-birth order | Fertility rate | 10–14 | 15–19 | | | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49^1^
Race and Hispanic origin of mother and live-birth order | Fertility rate | 10–14 | Total | 15–17 | 18–19 | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49^1^
All races and origins^2^
Total | 54.5 | 0.2 | 13.1 | 5.5 | 24.6 | 57.7 | 91.0 | 94.3 | 54.3 | 12.5 | 1.1
1st child | 21.4 | 0.2 | 11.3 | 5.1 | 20.6 | 33.1 | 37.1 | 30.4 | 13.0 | 2.7 | 0.3
2nd child | 17.1 | 0.0 | 1.6 | 0.3 | 3.6 | 17.4 | 29.6 | 31.5 | 17.9 | 3.5 | 0.3
3rd child | 9.0 | * | 0.2 | 0.0 | 0.4 | 5.5 | 15.2 | 17.9 | 11.5 | 2.5 | 0.2
4th child | 4.0 | * | 0.0 | * | 0.0 | 1.4 | 6.0 | 8.4 | 6.1 | 1.6 | 0.1
5th child | 1.7 | * | 0.0 | * | 0.0 | 0.3 | 2.1 | 3.5 | 2.9 | 0.9 | 0.1
6th and 7th child | 1.0 | * | * | * | * | 0.1 | 0.9 | 2.2 | 2.1 | 0.8 | 0.1
8th child or higher order | 0.4 | * | * | * | * | 0.0 | 0.1 | 0.5 | 0.9 | 0.5 | 0.1
Non-Hispanic, single race^3^
American Indian and Alaska Native | 48.0 | 0.3 | 20.9 | 9.4 | 38.6 | 73.2 | 78.7 | 64.0 | 36.1 | 8.4 | 0.6
1st child | 15.6 | 0.3 | 17.5 | 8.7 | 31.1 | 37.1 | 21.4 | 10.4 | 4.3 | 0.9 | *
2nd child | 12.7 | * | 3.0 | 0.7 | 6.7 | 23.4 | 23.9 | 15.5 | 6.8 | 1.3 | *
3rd child | 8.7 | * | 0.3 | * | 0.8 | 9.4 | 17.8 | 14.8 | 7.0 | 1.6 | *
4th child | 5.2 | * | * | * | * | 2.5 | 9.4 | 10.2 | 6.6 | 1.3 | *
5th child | 2.8 | * | * | * | * | 0.5 | 3.9 | 6.2 | 4.6 | 1.2 | *
6th and 7th child | 2.3 | * | * | * | * | 0.2 | 2.0 | 5.3 | 4.7 | 1.2 | *
8th child or higher order | 0.8 | * | * | * | * | * | 0.2 | 1.5 | 2.0 | 0.9 | *
Asian | 47.8 | * | 1.8 | 0.6 | 3.4 | 15.6 | 56.2 | 101.3 | 68.4 | 16.7 | 1.8
1st child | 22.1 | * | 1.6 | 0.6 | 2.9 | 10.5 | 33.8 | 49.7 | 22.4 | 4.9 | 0.7
2nd child | 17.2 | * | 0.2 | 0.0 | 0.4 | 3.8 | 15.3 | 36.5 | 29.8 | 6.3 | 0.5
3rd child | 5.6 | * | 0.0 | * | 0.1 | 0.9 | 4.8 | 10.1 | 10.6 | 3.2 | 0.3
4th child | 1.9 | * | * | * | * | 0.3 | 1.5 | 3.2 | 3.5 | 1.3 | 0.2
5th child | 0.7 | * | * | * | * | 0.1 | 0.5 | 1.1 | 1.3 | 0.5 | 0.1
6th and 7th child | 0.3 | * | * | * | * | 0.0 | 0.2 | 0.5 | 0.7 | 0.3 | 0.1
8th child or higher order | 0.1 | * | * | * | * | * | 0.0 | 0.1 | 0.2 | 0.1 | 0.0
Black | 53.7 | 0.3 | 19.3 | 8.9 | 35.5 | 69.7 | 85.3 | 76.5 | 49.7 | 13.9 | 1.5
1st child | 18.9 | 0.3 | 16.4 | 8.3 | 29.1 | 38.5 | 28.1 | 17.4 | 9.1 | 2.5 | 0.4
2nd child | 15.1 | 0.0 | 2.5 | 0.6 | 5.6 | 20.5 | 26.8 | 22.0 | 13.1 | 3.3 | 0.4
3rd child | 9.6 | * | 0.3 | 0.0 | 0.7 | 7.5 | 16.5 | 17.1 | 11.5 | 3.0 | 0.2
4th child | 5.2 | * | 0.0 | * | 0.1 | 2.4 | 8.1 | 10.0 | 7.4 | 2.1 | 0.2
5th child | 2.5 | * | * | * | * | 0.6 | 3.5 | 5.0 | 3.9 | 1.2 | 0.1
6th and 7th child | 1.8 | * | * | * | * | 0.2 | 1.9 | 3.8 | 3.2 | 1.1 | 0.1
8th child or higher order | 0.6 | * | * | * | * | 0.0 | 0.3 | 1.0 | 1.4 | 0.6 | 0.1
Native Hawaiian and Pacific Islander | 73.2 | * | 21.2 | 7.5 | 41.4 | 115.3 | 137.3 | 95.8 | 56.7 | 15.8 | 1.4
1st child | 21.2 | * | 17.5 | 7.0 | 32.9 | 54.8 | 34.6 | 17.0 | 6.7 | 1.7 | *
2nd child | 18.0 | * | 3.3 | * | 7.7 | 36.2 | 36.8 | 20.9 | 10.6 | 2.6 | *
3rd child | 13.5 | * | * | * | * | 17.8 | 31.3 | 19.2 | 10.0 | 2.4 | *
4th child | 9.0 | * | * | * | * | 4.8 | 20.6 | 15.0 | 9.6 | 2.9 | *
5th child | 5.3 | * | * | * | * | 1.1 | 8.5 | 10.6 | 8.4 | 1.7 | *
6th and 7th child | 4.6 | * | * | * | * | 0.6 | 4.7 | 10.2 | 7.9 | 2.5 | *
8th child or higher order | 1.7 | * | * | * | * | * | 0.7 | 2.9 | 3.6 | 2.1 | *
White | 51.7 | 0.1 | 8.4 | 2.9 | 16.7 | 48.3 | 89.2 | 97.1 | 51.9 | 10.6 | 0.9
1st child | 20.9 | 0.1 | 7.4 | 2.7 | 14.2 | 28.4 | 39.7 | 33.8 | 13.4 | 2.5 | 0.3
2nd child | 17.0 | * | 1.0 | 0.2 | 2.2 | 14.3 | 29.0 | 34.2 | 18.2 | 3.2 | 0.2
3rd child | 8.1 | * | 0.1 | 0.0 | 0.2 | 4.4 | 13.2 | 17.1 | 10.7 | 2.0 | 0.1
4th child | 3.3 | * | 0.0 | * | 0.0 | 1.0 | 4.9 | 7.1 | 4.9 | 1.1 | 0.1
5th child | 1.3 | * | * | * | * | 0.2 | 1.6 | 2.8 | 2.1 | 0.6 | 0.1
6th and 7th child | 0.8 | * | * | * | * | 0.0 | 0.6 | 1.8 | 1.7 | 0.6 | 0.1
8th child or higher order | 0.4 | * | * | * | * | 0.0 | 0.1 | 0.4 | 0.9 | 0.6 | 0.1
Hispanic^4^
Total | 64.7 | 0.3 | 20.8 | 9.3 | 39.0 | 81.1 | 111.2 | 100.3 | 59.0 | 15.4 | 1.1
1st child | 24.3 | 0.3 | 17.9 | 8.7 | 32.5 | 45.8 | 39.2 | 25.4 | 11.1 | 2.3 | 0.3
2nd child | 19.3 | 0.0 | 2.6 | 0.6 | 5.8 | 25.2 | 37.7 | 30.9 | 15.9 | 3.4 | 0.2
3rd child | 11.7 | * | 0.3 | 0.0 | 0.6 | 7.8 | 22.0 | 23.8 | 14.3 | 3.5 | 0.2
4th child | 5.6 | * | 0.0 | * | 0.1 | 1.8 | 8.5 | 12.2 | 9.3 | 2.8 | 0.2
5th child | 2.3 | * | 0.0 | * | 0.0 | 0.4 | 2.6 | 4.9 | 4.7 | 1.7 | 0.1
6th and 7th child | 1.3 | * | * | * | * | 0.1 | 1.0 | 2.5 | 3.0 | 1.3 | 0.1
8th child or higher order | 0.3 | * | * | * | * | 0.0 | 0.1 | 0.5 | 0.7 | 0.5 | 0.0

0.0 Quantity more than zero but less than 0.05.

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Birth rates computed by relating births to women age 45 and older to women ages 45–49; see Technical Notes in this report.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic females are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 6 Births, by race and Hispanic origin of mother: United States, each state and territory, 2023

[By place of residence]

Area | All races and origins^2^ | Non-Hispanic, single race^1^ | | | | | Hispanic^3^
Area | All races and origins^2^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian and Pacific Islander | White | Hispanic^3^
United States^4^ | 3,596,017 | 24,571 | 215,738 | 491,494 | 10,115 | 1,787,051 | 945,200
Alabama | 57,858 | 139 | 820 | 15,543 | 62 | 33,230 | 6,890
Alaska | 9,015 | 1,706 | 487 | 212 | 310 | 4,353 | 793
Arizona | 78,096 | 3,346 | 2,855 | 4,334 | 234 | 29,694 | 35,183
Arkansas | 35,264 | 205 | 813 | 6,379 | 534 | 22,163 | 4,305
California | 400,108 | 1,169 | 55,780 | 18,340 | 1,453 | 104,381 | 194,939
Colorado | 61,494 | 310 | 2,498 | 2,904 | 256 | 33,640 | 19,544
Connecticut | 34,559 | 34 | 1,850 | 4,053 | * | 17,969 | 9,803
Delaware | 10,427 | 17 | 621 | 2,694 | * | 4,702 | 2,015
District of Columbia | 7,896 | 10 | 347 | 3,362 | * | 2,570 | 1,413
Florida | 221,410 | 239 | 6,789 | 44,898 | 169 | 90,118 | 75,987
Georgia | 125,120 | 102 | 5,719 | 41,118 | 119 | 52,541 | 22,003
Hawaii | 14,808 | 31 | 3,524 | 313 | 1,396 | 2,806 | 2,610
Idaho | 22,397 | 174 | 398 | 291 | 63 | 16,649 | 4,265
Illinois | 124,820 | 97 | 8,416 | 18,013 | 28 | 64,698 | 30,465
Indiana | 79,000 | 68 | 2,433 | 10,035 | 69 | 53,866 | 10,586
Iowa | 36,052 | 142 | 956 | 2,613 | 420 | 26,961 | 4,211
Kansas | 34,065 | 142 | 1,028 | 2,211 | 84 | 23,088 | 6,576
Kentucky | 51,984 | 59 | 1,136 | 4,936 | 100 | 39,667 | 4,852
Louisiana | 54,927 | 267 | 953 | 19,625 | 27 | 27,223 | 5,964
Maine | 11,627 | 70 | 199 | 790 | * | 10,015 | 334
Maryland | 65,594 | 75 | 4,262 | 18,939 | 29 | 25,746 | 14,442
Massachusetts | 67,093 | 59 | 5,268 | 7,300 | 21 | 36,028 | 15,700
Michigan | 99,124 | 316 | 4,072 | 16,320 | 38 | 67,719 | 7,555
Minnesota | 61,715 | 742 | 4,666 | 7,415 | 78 | 40,406 | 6,498
Mississippi | 34,459 | 236 | 456 | 13,896 | 13 | 17,357 | 2,122
Missouri | 67,123 | 169 | 1,543 | 8,506 | 260 | 48,538 | 5,518
Montana | 11,078 | 915 | 110 | 60 | * | 8,883 | 703
Nebraska | 24,111 | 297 | 823 | 1,506 | 52 | 15,656 | 5,010
Nevada | 31,794 | 208 | 2,461 | 4,093 | 325 | 10,448 | 12,631
New Hampshire | 11,936 | 10 | 411 | 304 | * | 10,094 | 889
New Jersey | 101,001 | 45 | 9,983 | 12,030 | 33 | 46,205 | 30,238
New Mexico | 20,951 | 2,063 | 393 | 381 | 16 | 5,232 | 12,461
New York | 203,612 | 325 | 20,000 | 26,192 | 50 | 101,336 | 50,832
North Carolina | 120,082 | 1,309 | 4,920 | 25,135 | 137 | 61,143 | 23,788
North Dakota | 9,647 | 603 | 232 | 550 | 35 | 6,946 | 759
Ohio | 126,896 | 72 | 3,862 | 20,107 | 134 | 88,799 | 9,748
Oklahoma | 47,909 | 4,093 | 1,329 | 3,683 | 236 | 25,483 | 8,809
Oregon | 38,298 | 345 | 1,976 | 1,003 | 372 | 22,671 | 8,881
Pennsylvania | 126,951 | 141 | 6,028 | 15,766 | 42 | 82,284 | 18,505
Rhode Island | 9,805 | 27 | 393 | 797 | * | 5,266 | 3,008
South Carolina | 57,729 | 150 | 1,186 | 14,746 | 83 | 31,884 | 7,957
South Dakota | 11,201 | 1,362 | 207 | 345 | 12 | 8,003 | 836
Tennessee | 83,021 | 107 | 1,804 | 14,377 | 88 | 52,962 | 11,895
Texas | 387,945 | 630 | 21,694 | 47,140 | 607 | 119,189 | 191,967
Utah | 45,019 | 342 | 1,155 | 653 | 580 | 31,629 | 9,236
Vermont | 5,065 | 12 | 143 | 123 | * | 4,526 | 152
Virginia | 92,649 | 111 | 6,810 | 17,607 | 115 | 49,171 | 16,222
Washington | 80,932 | 828 | 9,032 | 3,653 | 1,348 | 42,237 | 17,145
West Virginia | 16,606 | 16 | 178 | 573 | * | 14,852 | 506
Wisconsin | 59,754 | 486 | 2,651 | 5,592 | 22 | 41,471 | 7,591
Wyoming | 5,990 | 150 | 68 | 38 | * | 4,553 | 858
Puerto Rico | 18,601 | * | 24 | 52 | * | 364 | 18,146
Virgin Islands | 823 | * | * | 549 | * | 88 | 166
Guam | 2,353 | * | 556 | 27 | 1,510 | 115 | 31
American Samoa | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 579 | * | 210 | * | 318 | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

--- Data not available.

1 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, as well as non-Hispanic multiple-race women, and births with origin not stated.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

4 Excludes data for the territories.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 7 Births, by Hispanic origin of mother: United States, each state and territory, 2023

[By place of residence]

Area | Total | Central and South American | Cuban | Dominican | Mexican | Puerto Rican | Other and unknown Hispanic
United States^1^ | 945,200 | 208,618 | 30,001 | 33,575 | 508,127 | 66,203 | 98,676
Alabama | 6,890 | 2,871 | 81 | 49 | 3,490 | 283 | 116
Alaska | 793 | 82 | 27 | 47 | 421 | 113 | 103
Arizona | 35,183 | 1,699 | 322 | 95 | 30,069 | 602 | 2,396
Arkansas | 4,305 | 789 | 35 | 13 | 2,747 | 120 | 601
California | 194,939 | 23,842 | 755 | 206 | 143,021 | 2,008 | 25,107
Colorado | 19,544 | 2,259 | 224 | 54 | 13,014 | 559 | 3,434
Connecticut | 9,803 | 3,262 | 138 | 1,001 | 787 | 3,923 | 692
Delaware | 2,015 | 667 | 25 | 75 | 672 | 416 | 160
District of Columbia | 1,413 | 922 | 35 | 37 | 142 | 42 | 235
Florida | 75,987 | 26,972 | 17,637 | 3,548 | 11,509 | 12,741 | 3,580
Georgia | 22,003 | 5,187 | 488 | 386 | 12,469 | 1,368 | 2,105
Hawaii | 2,610 | 159 | 31 | 24 | 883 | 839 | 674
Idaho | 4,265 | 368 | 30 | * | 3,047 | 72 | 740
Illinois | 30,465 | 4,325 | 250 | 133 | 22,965 | 1,950 | 842
Indiana | 10,586 | 2,704 | 136 | 91 | 5,751 | 555 | 1,349
Iowa | 4,211 | 918 | 91 | 22 | 2,795 | 145 | 240
Kansas | 6,576 | 1,166 | 76 | 21 | 4,699 | 194 | 420
Kentucky | 4,852 | 1,387 | 805 | 37 | 1,947 | 295 | 381
Louisiana | 5,964 | 3,339 | 115 | 94 | 1,269 | 174 | 973
Maine | 334 | 96 | 10 | 15 | 97 | 91 | 25
Maryland | 14,442 | 10,484 | 146 | 448 | 1,626 | 691 | 1,047
Massachusetts | 15,700 | 4,811 | 175 | 3,520 | 540 | 3,838 | 2,816
Michigan | 7,555 | 828 | 221 | 78 | 5,320 | 448 | 660
Minnesota | 6,498 | 1,869 | 76 | 53 | 3,781 | 236 | 483
Mississippi | 2,122 | 791 | 30 | 19 | 898 | 125 | 259
Missouri | 5,518 | 1,415 | 148 | 51 | 2,997 | 268 | 639
Montana | 703 | 83 | * | * | 472 | 32 | 102
Nebraska | 5,010 | 1,450 | 239 | 17 | 2,931 | 118 | 255
Nevada | 12,631 | 1,683 | 616 | 42 | 9,083 | 392 | 815
New Hampshire | 889 | 162 | 19 | 113 | 100 | 214 | 281
New Jersey | 30,238 | 12,498 | 779 | 5,608 | 4,243 | 5,069 | 2,041
New Mexico | 12,461 | 264 | 85 | * | 6,644 | 107 | 5,354
New York | 50,832 | 20,032 | 590 | 10,708 | 6,289 | 8,608 | 4,605
North Carolina | 23,788 | 8,218 | 473 | 694 | 10,878 | 2,032 | 1,493
North Dakota | 759 | 74 | 14 | * | 527 | 48 | 90
Ohio | 9,748 | 3,035 | 112 | 279 | 3,625 | 1,982 | 715
Oklahoma | 8,809 | 1,372 | 103 | 24 | 6,056 | 245 | 1,009
Oregon | 8,881 | 1,124 | 132 | 26 | 6,350 | 209 | 1,040
Pennsylvania | 18,505 | 3,434 | 353 | 3,801 | 2,525 | 7,037 | 1,355
Rhode Island | 3,008 | 984 | 26 | 982 | 177 | 671 | 168
South Carolina | 7,957 | 2,872 | 166 | 136 | 3,224 | 702 | 857
South Dakota | 836 | 269 | 17 | * | 427 | 55 | 64
Tennessee | 11,895 | 5,191 | 237 | 87 | 4,818 | 512 | 1,050
Texas | 191,967 | 25,325 | 3,372 | 556 | 135,656 | 2,969 | 24,089
Utah | 9,236 | 2,478 | 53 | 71 | 5,932 | 185 | 517
Vermont | 152 | 41 | * | * | 52 | 34 | 16
Virginia | 16,222 | 11,186 | 248 | 134 | 3,194 | 1,256 | 204
Washington | 17,145 | 2,110 | 166 | 67 | 12,495 | 483 | 1,824
West Virginia | 506 | 160 | 11 | * | 186 | 85 | 61
Wisconsin | 7,591 | 1,299 | 67 | 70 | 4,733 | 1,040 | 382
Wyoming | 858 | 62 | * | * | 554 | 22 | 212
Puerto Rico | 18,146 | 150 | 19 | 385 | 35 | 17,549 | *
Virgin Islands | 166 | 12 | * | 52 | * | 12 | 88
Guam | 31 | * | * | * | 22 | * | *
American Samoa | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | * | * | * | * | * | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

--- Data not available.

1 Excludes data for the territories.

NOTES: In this table, Hispanic women are classified by place of origin; non-Hispanic women are not shown. Other and unknown Hispanic includes origins not otherwise classified, including Spaniard. See Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 8 Birth rates, by age of mother: United States, each state and territory, 2023

[By place of residence. Fertility rates are births per 1,000 females ages 15–44; total fertility rates are sums of birth rates for 5-year age groups multiplied by 5; birth rates by age are births per 1,000 women in specified age group estimated in each area. Populations estimated as of July 1

Area | Birth rate | Fertility rate | Total fertility rate | Age of mother
Area | Birth rate | Fertility rate | Total fertility rate | 10–14 | 15–19 | | | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49^1^
Area | Birth rate | Fertility rate | Total fertility rate | 10–14 | Total | 15–17 | 18–19 | 20–24 | 25–29 | 30–34 | 35–39 | 40–44 | 45–49^1^
United States^2^ | 10.7 | 54.5 | 1,621.0 | 0.2 | 13.1 | 5.5 | 24.6 | 57.7 | 91.0 | 94.3 | 54.3 | 12.5 | 1.1
Alabama | 11.3 | 57.9 | 1,734.5 | 0.3 | 20.1 | 8.7 | 36.6 | 81.8 | 111.0 | 85.0 | 40.2 | 8.0 | 0.5
Alaska | 12.3 | 62.4 | 1,832.5 | * | 16.0 | 4.8 | 37.1 | 84.0 | 106.5 | 92.3 | 53.9 | 12.4 | 1.2
Arizona | 10.5 | 54.2 | 1,602.0 | 0.1 | 14.3 | 5.9 | 27.0 | 61.0 | 94.7 | 89.2 | 49.2 | 11.1 | 0.8
Arkansas | 11.5 | 59.2 | 1,775.0 | 0.4 | 23.8 | 9.8 | 46.4 | 91.2 | 114.0 | 80.5 | 37.1 | 7.6 | 0.4
California | 10.3 | 50.4 | 1,480.5 | 0.1 | 9.1 | 3.7 | 17.1 | 43.1 | 72.7 | 89.4 | 63.1 | 16.8 | 1.8
Colorado | 10.5 | 50.2 | 1,454.0 | 0.1 | 10.9 | 4.9 | 19.9 | 49.6 | 74.4 | 88.1 | 54.6 | 12.0 | 1.1
Connecticut | 9.6 | 50.2 | 1,517.0 | * | 6.8 | 2.8 | 12.3 | 31.6 | 72.8 | 109.4 | 66.7 | 14.7 | 1.3
Delaware | 10.1 | 54.4 | 1,633.5 | * | 13.5 | 5.9 | 24.0 | 57.5 | 90.8 | 95.9 | 54.2 | 13.9 | 0.8
District of Columbia | 11.6 | 43.0 | 1,197.0 | * | 12.3 | 10.0 | 14.0 | 33.1 | 34.8 | 64.5 | 68.8 | 22.6 | 2.9
Florida | 9.8 | 53.9 | 1,601.0 | 0.2 | 12.7 | 5.3 | 24.1 | 55.4 | 89.9 | 92.5 | 55.1 | 13.3 | 1.1
Georgia | 11.3 | 54.9 | 1,644.5 | 0.3 | 16.5 | 6.9 | 31.9 | 66.9 | 95.2 | 88.6 | 48.7 | 11.8 | 0.9
Hawaii | 10.3 | 56.9 | 1,681.0 | * | 11.3 | 4.0 | 23.5 | 64.3 | 89.7 | 90.2 | 61.6 | 17.8 | 1.3
Idaho | 11.4 | 57.6 | 1,793.0 | * | 10.5 | 3.6 | 19.3 | 74.5 | 120.9 | 96.5 | 46.0 | 9.4 | 0.7
Illinois | 9.9 | 50.4 | 1,502.5 | 0.2 | 10.7 | 4.3 | 20.9 | 46.5 | 78.8 | 95.8 | 55.3 | 12.2 | 1.0
Indiana | 11.5 | 58.9 | 1,765.0 | 0.2 | 15.7 | 6.0 | 31.2 | 72.4 | 114.3 | 95.0 | 45.3 | 9.4 | 0.7
Iowa | 11.2 | 59.0 | 1,813.0 | 0.1 | 11.8 | 5.1 | 21.7 | 58.5 | 124.1 | 110.5 | 48.0 | 9.0 | 0.6
Kansas | 11.6 | 59.5 | 1,812.0 | 0.2 | 15.1 | 6.1 | 29.0 | 67.4 | 115.3 | 105.5 | 48.4 | 9.7 | 0.8
Kentucky | 11.5 | 60.4 | 1,804.5 | 0.2 | 20.7 | 7.8 | 42.3 | 87.4 | 114.7 | 87.6 | 41.5 | 8.3 | 0.5
Louisiana | 12.0 | 60.4 | 1,829.0 | 0.5 | 23.1 | 9.4 | 45.2 | 88.6 | 113.7 | 87.1 | 43.2 | 9.1 | 0.5
Maine | 8.3 | 47.0 | 1,399.5 | * | 7.2 | 2.0 | 14.5 | 46.2 | 81.8 | 87.8 | 46.6 | 9.7 | 0.5
Maryland | 10.6 | 54.1 | 1,614.0 | 0.2 | 10.8 | 4.7 | 20.5 | 47.1 | 82.5 | 102.0 | 62.7 | 15.7 | 1.8
Massachusetts | 9.6 | 47.4 | 1,394.5 | 0.1 | 5.8 | 2.8 | 9.5 | 26.1 | 57.9 | 104.2 | 68.4 | 15.0 | 1.4
Michigan | 9.9 | 52.2 | 1,547.5 | 0.1 | 10.9 | 4.0 | 21.2 | 49.4 | 94.4 | 95.9 | 48.7 | 9.4 | 0.7
Minnesota | 10.8 | 55.7 | 1,687.0 | 0.1 | 7.8 | 3.1 | 15.3 | 43.4 | 97.7 | 116.3 | 58.9 | 11.9 | 1.3
Mississippi | 11.7 | 59.2 | 1,791.5 | 0.3 | 24.9 | 11.7 | 45.5 | 92.5 | 116.7 | 81.0 | 35.8 | 6.7 | 0.4
Missouri | 10.8 | 55.8 | 1,669.5 | 0.2 | 15.9 | 6.6 | 30.9 | 68.4 | 104.4 | 91.5 | 44.1 | 8.8 | 0.6
Montana | 9.8 | 52.2 | 1,555.5 | * | 11.8 | 4.7 | 23.7 | 55.0 | 97.0 | 91.0 | 46.7 | 9.0 | 0.5
Nebraska | 12.2 | 62.5 | 1,913.0 | 0.2 | 13.1 | 5.4 | 25.0 | 59.9 | 123.4 | 119.7 | 55.2 | 10.3 | 0.8
Nevada | 10.0 | 50.8 | 1,499.0 | 0.2 | 13.1 | 5.0 | 28.1 | 63.0 | 84.9 | 79.2 | 46.6 | 11.9 | 0.9
New Hampshire | 8.5 | 46.8 | 1,381.0 | * | 4.6 | 1.5 | 8.7 | 29.6 | 76.3 | 101.9 | 52.3 | 10.9 | 0.6
New Jersey | 10.9 | 57.4 | 1,703.5 | 0.1 | 7.5 | 3.2 | 14.8 | 41.6 | 78.9 | 117.7 | 75.6 | 17.7 | 1.6
New Mexico | 9.9 | 51.5 | 1,551.0 | 0.2 | 17.9 | 8.1 | 33.1 | 71.1 | 94.8 | 75.5 | 40.9 | 9.3 | 0.5
New York | 10.4 | 52.7 | 1,532.5 | 0.1 | 8.5 | 3.5 | 15.4 | 45.5 | 70.9 | 94.8 | 66.5 | 18.4 | 1.8
North Carolina | 11.1 | 56.0 | 1,663.5 | 0.2 | 14.8 | 6.1 | 27.5 | 63.7 | 96.8 | 94.1 | 51.4 | 11.0 | 0.7
North Dakota | 12.3 | 62.0 | 1,848.5 | * | 11.2 | 5.4 | 18.5 | 54.0 | 126.1 | 117.4 | 49.9 | 10.3 | 0.7
Ohio | 10.8 | 56.4 | 1,678.0 | 0.2 | 14.6 | 5.9 | 28.4 | 66.5 | 101.8 | 94.7 | 47.8 | 9.3 | 0.7
Oklahoma | 11.8 | 59.1 | 1,775.5 | 0.2 | 20.6 | 8.3 | 39.9 | 86.5 | 113.7 | 85.3 | 39.9 | 8.5 | 0.4
Oregon | 9.0 | 45.9 | 1,352.0 | * | 9.4 | 3.7 | 18.5 | 46.4 | 76.8 | 77.8 | 48.1 | 11.0 | 0.8
Pennsylvania | 9.8 | 51.9 | 1,550.0 | 0.2 | 9.8 | 4.7 | 16.6 | 48.7 | 87.7 | 98.0 | 53.4 | 11.3 | 0.9
Rhode Island | 8.9 | 45.2 | 1,336.0 | * | 7.5 | 3.3 | 11.9 | 33.9 | 67.8 | 90.1 | 54.8 | 11.9 | 0.9
South Carolina | 10.7 | 55.8 | 1,672.0 | 0.2 | 17.1 | 7.7 | 31.3 | 67.5 | 101.9 | 90.0 | 46.9 | 10.0 | 0.8
South Dakota | 12.2 | 65.6 | 2,000.0 | * | 16.6 | 7.2 | 31.9 | 69.8 | 133.2 | 120.4 | 49.3 | 9.9 | 0.5
Tennessee | 11.6 | 58.9 | 1,733.0 | 0.2 | 20.4 | 8.0 | 41.0 | 78.6 | 103.3 | 88.6 | 45.5 | 9.5 | 0.5
Texas | 12.7 | 60.6 | 1,813.5 | 0.3 | 19.4 | 8.6 | 37.0 | 75.7 | 105.1 | 97.3 | 51.9 | 12.0 | 1.0
Utah | 13.2 | 59.6 | 1,800.5 | * | 8.7 | 3.4 | 17.0 | 58.3 | 125.3 | 105.1 | 50.9 | 10.7 | 1.0
Vermont | 7.8 | 42.1 | 1,287.0 | * | 5.7 | 2.2 | 9.6 | 27.9 | 69.9 | 90.0 | 53.3 | 9.7 | 0.9
Virginia | 10.6 | 53.6 | 1,600.0 | 0.1 | 10.9 | 4.4 | 20.4 | 50.8 | 86.7 | 99.3 | 57.4 | 13.5 | 1.3
Washington | 10.4 | 51.4 | 1,486.0 | 0.1 | 9.7 | 3.6 | 20.0 | 50.8 | 79.8 | 87.8 | 54.6 | 13.2 | 1.2
West Virginia | 9.4 | 53.1 | 1,602.5 | 0.2 | 18.5 | 6.3 | 37.2 | 83.2 | 107.1 | 72.0 | 32.8 | 6.2 | 0.5
Wisconsin | 10.1 | 53.6 | 1,628.0 | 0.1 | 9.9 | 4.2 | 18.5 | 46.3 | 99.9 | 108.6 | 50.7 | 9.5 | 0.6
Wyoming | 10.3 | 54.5 | 1,683.0 | * | 12.6 | 4.8 | 25.5 | 75.3 | 110.6 | 88.3 | 40.9 | 8.0 | 0.9
Puerto Rico | 5.8 | 30.5 | 894.0 | * | 12.3 | 4.6 | 23.5 | 52.2 | 52.2 | 36.5 | 21.2 | 4.2 | 0.2
U.S. Virgin Islands | 7.8 | 44.5 | 1,367.5 | * | 11.6 | * | 25.1 | 65.0 | 75.5 | 75.4 | 36.1 | 9.3 | *
Guam | 13.9 | 71.7 | 2,114.5 | * | 23.5 | 10.9 | 44.0 | 81.7 | 115.5 | 114.5 | 63.4 | 23.5 | *
American Samoa | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 11.3 | 63.8 | 2,132.5 | * | 16.9 | 9.5 | 30.3 | 58.7 | 90.8 | 125.0 | 107.6 | 25.1 | *

* Estimate does not meet National Center for Health Statistics standards of reliability.

--- Data not available.

1 Birth rates computed by relating births to women age 45 and older to women ages 45–49; see Technical Notes in this report.

2 Excludes data for the territories.

NOTES: Population data for computing birth rates were provided by the U.S. Census Bureau. Rates by state may differ from rates computed on the basis of other population estimates.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 9 Births to unmarried women, by age and race and Hispanic origin of mother: United States, 2023

Age of mother | All races and origins^2^ | Non-Hispanic, single race^1^
Age of mother | All races and origins^2^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian and Pacific Islander | White | Hispanic^3^
| Number
All ages | 1,440,031 | 16,877 | 25,961 | 340,748 | 5,327 | 479,646 | 511,844
Younger than 15 | 1,760 | 22 | * | 486 | * | 350 | 795
15–19 | 129,491 | 1,757 | 678 | 27,898 | 408 | 39,331 | 53,205
15–17 | 35,062 | 497 | 170 | 7,984 | 95 | 8,958 | 15,552
18–19 | 94,429 | 1,260 | 508 | 19,914 | 313 | 30,373 | 37,653
20–24 | 420,592 | 5,132 | 3,568 | 93,267 | 1,715 | 145,488 | 153,101
25–29 | 403,054 | 4,433 | 6,800 | 96,945 | 1,586 | 133,438 | 143,102
30–34 | 295,564 | 3,523 | 7,666 | 77,152 | 950 | 96,874 | 98,305
35–39 | 148,336 | 1,653 | 5,280 | 35,839 | 518 | 50,285 | 49,321
40 and older | 39,068 | 340 | 1,858 | 8,595 | 144 | 13,044 | 13,442
| Percent
All ages | 40.0 | 68.7 | 12.0 | 69.3 | 52.7 | 26.8 | 54.2
Younger than 15 | 99.7 | * | * | 100.0 | * | 99.7 | 99.4
15–19 | 91.9 | 95.4 | 73.3 | 98.2 | 88.9 | 87.6 | 91.9
15–17 | 98.2 | 98.8 | 89.5 | 99.7 | 97.9 | 97.1 | 97.9
18–19 | 89.7 | 94.2 | 69.1 | 97.6 | 86.5 | 85.1 | 89.6
20–24 | 68.2 | 81.7 | 37.9 | 90.5 | 70.8 | 55.2 | 73.7
25–29 | 40.9 | 64.8 | 16.7 | 73.6 | 52.3 | 26.6 | 52.9
30–34 | 26.9 | 59.0 | 8.7 | 58.7 | 39.4 | 16.3 | 40.9
35–39 | 24.5 | 56.2 | 8.7 | 48.1 | 37.0 | 16.0 | 37.5
40 and older | 26.6 | 51.0 | 12.2 | 39.4 | 37.0 | 19.4 | 37.0

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Race groups are non-Hispanic, single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

NOTE: For New York, mother's marital status is inferred; see reference 9 in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 10 Birth rates for unmarried women: United States, 2010–2023, and by age and race and Hispanic origin of mother: United States, 2016–2023

[Rates are births to unmarried women per 1,000 unmarried women. Populations estimated as of July 1 for all years]

Race and Hispanic origin and year | Fertility rate^1^ | Age of mother
Race and Hispanic origin and year | Fertility rate^1^ | 15–19 | | | 20–24 | 25–29 | 30–34 | 35–39 | 40–44^2^
Race and Hispanic origin and year | Fertility rate^1^ | Total | 15–17 | 18–19 | 20–24 | 25–29 | 30–34 | 35–39 | 40–44^2^
All races^3^
2023 | 36.4 | 12.3 | 5.5 | 22.7 | 44.6 | 57.4 | 57.5 | 38.8 | 11.8
2022 | 37.2 | 12.7 | 5.6 | 23.6 | 44.0 | 58.4 | 58.6 | 38.8 | 11.6
2021 | 37.8 | 13.0 | 5.6 | 24.4 | 47.4 | 58.7 | 58.5 | 38.2 | 11.4
2020 | 38.4 | 14.0 | 6.1 | 26.0 | 49.2 | 59.9 | 58.3 | 36.9 | 11.3
2019 | 39.9 | 15.4 | 6.6 | 28.3 | 51.6 | 61.5 | 60.6 | 36.0 | 11.1
2018 | 40.1 | 16.0 | 7.1 | 29.2 | 52.2 | 62.8 | 59.5 | 35.2 | 10.6
2017 | 41.0 | 17.1 | 7.7 | 31.4 | 54.2 | 64.4 | 57.9 | 36.0 | 10.1
2016 | 42.4 | 18.5 | 8.6 | 33.5 | 56.6 | 65.8 | 59.2 | 35.6 | 10.0
2015 | 43.4 | 20.2 | 9.6 | 36.5 | 59.7 | 66.9 | 60.3 | 34.1 | 9.0
2014 | 43.9 | 22.0 | 10.6 | 39.4 | 61.6 | 67.6 | 58.1 | 33.4 | 8.5
2013 | 44.3 | 24.0 | 11.9 | 42.1 | 63.1 | 66.7 | 56.6 | 31.8 | 8.3
2012 | 45.3 | 26.7 | 13.7 | 45.8 | 64.7 | 67.2 | 56.3 | 30.9 | 8.5
2011 | 46.0 | 28.4 | 14.9 | 48.2 | 66.7 | 67.8 | 56.2 | 29.9 | 8.2
2010 | 47.5 | 31.1 | 16.8 | 52.0 | 70.0 | 69.2 | 56.3 | 29.6 | 8.0
Non-Hispanic, single race^4^
Black:
2023 | 48.8 | 19.4 | 9.1 | 35.6 | 67.1 | 74.8 | 65.6 | 40.5 | 12.0
2022 | 50.2 | 20.3 | 9.1 | 37.6 | 67.6 | 78.9 | 64.8 | 38.5 | 11.8
2021 | 52.1 | 21.8 | 9.4 | 40.8 | 76.8 | 82.9 | 63.9 | 36.7 | 10.7
2020 | 54.6 | 23.7 | 10.6 | 43.2 | 80.8 | 88.3 | 65.1 | 37.0 | 10.4
2019 | 56.7 | 25.7 | 11.3 | 46.2 | 83.5 | 87.4 | 68.4 | 37.5 | 10.5
2018 | 56.4 | 26.1 | 12.0 | 46.1 | 85.0 | 85.9 | 68.2 | 35.6 | 9.7
2017 | 57.5 | 27.3 | 12.6 | 48.7 | 88.8 | 89.3 | 66.2 | 35.1 | 8.9
2016 | 57.9 | 29.0 | 13.9 | 51.2 | 90.0 | 89.6 | 64.4 | 33.8 | 8.9
White:
2023 | 24.9 | 7.5 | 2.9 | 14.6 | 30.6 | 39.7 | 40.3 | 27.8 | 8.1
2022 | 25.8 | 8.1 | 3.1 | 15.5 | 30.7 | 40.7 | 42.8 | 28.6 | 7.9
2021 | 27.0 | 8.4 | 3.1 | 16.3 | 33.8 | 42.1 | 45.2 | 29.3 | 8.1
2020 | 27.5 | 9.0 | 3.3 | 17.5 | 35.1 | 42.8 | 45.1 | 27.8 | 8.2
2019 | 28.6 | 10.0 | 3.7 | 19.3 | 36.7 | 44.8 | 45.7 | 27.0 | 7.9
2018 | 28.8 | 10.6 | 4.0 | 20.3 | 37.6 | 45.7 | 43.9 | 25.9 | 7.5
2017 | 29.2 | 11.5 | 4.4 | 22.1 | 38.9 | 46.2 | 41.9 | 25.3 | 7.2
2016 | 30.3 | 12.4 | 5.0 | 23.5 | 40.9 | 47.3 | 43.0 | 25.2 | 6.8
Hispanic^5^
2023 | 57.2 | 19.6 | 9.3 | 35.9 | 69.9 | 93.0 | 92.2 | 64.2 | 21.0
2022 | 57.4 | 20.0 | 9.3 | 36.8 | 66.6 | 92.0 | 93.0 | 65.2 | 21.4
2021 | 55.7 | 19.7 | 9.2 | 36.4 | 68.0 | 87.0 | 88.7 | 61.9 | 21.4
2020 | 55.5 | 21.2 | 10.1 | 38.7 | 69.3 | 87.9 | 84.8 | 59.4 | 20.2
2019 | 57.9 | 23.2 | 11.3 | 41.5 | 73.8 | 90.6 | 91.5 | 55.8 | 20.0
2018 | 59.5 | 24.4 | 12.2 | 43.4 | 74.6 | 95.7 | 96.1 | 57.4 | 20.0
2017 | 62.5 | 26.3 | 13.3 | 47.0 | 78.6 | 102.3 | 98.7 | 64.2 | 18.7
2016 | 66.0 | 29.2 | 15.1 | 51.2 | 83.1 | 106.4 | 103.6 | 65.0 | 19.3

1 Computed by relating total births to unmarried mothers, regardless of age, to unmarried females ages 15–44.

2 Rates computed by relating births to unmarried women age 40 and older to unmarried women ages 40–44; see Technical Notes in this report.

3 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

4 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

5 Includes all people of Hispanic origin of any race; see Technical Notes.

NOTES: Rates for 2020 have been revised and may differ from those published in ‘‘Births: Final Data for 2020”; see Technical Notes. For New York, mother's marital status is inferred; see reference 9 in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 11 Selected demographic characteristics of births, by race and Hispanic origin of mother: United States, 2023

[Birth rates are births per 1,000 population. Fertility rates are computed by relating total births, regardless of age of mother, to females ages 15–44. Total fertility rates are sums of birth rates for 5-year age groups multiplied by 5. Unmarried rates are births to unmarried females per 1,000 unmarried females. Populations estimated as of July 1. Mean age at first birth is the arithmetic average of the age of mothers at the time of birth, computed directly from the frequency of first births by age of mother]

Characteristic | All races and origins^2^ | Non-Hispanic, single race^1^
Characteristic | All races and origins^2^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian and Pacific Islander | White | Hispanic^3^
| Number
Births | 3,596,017 | 24,571 | 215,738 | 491,494 | 10,115 | 1,787,051 | 945,200
| Rate
Birth rate | 10.7 | 10.3 | 10.7 | 11.7 | 16.1 | 9.3 | 14.5
Fertility rate | 54.5 | 48.0 | 47.8 | 53.7 | 73.2 | 51.7 | 64.7
Total fertility rate | 1,621.0 | 1,411.0 | 1,309.0 | 1,581.0 | 2,218.0 | 1,532.5 | 1,946.0
Unmarried rate | 36.4 | 49.8 | 12.1 | 48.8 | 65.7 | 24.9 | 57.2
| Ratio
Sex ratio^4^ | 1,048 | 1,036 | 1,071 | 1,035 | 1,012 | 1,052 | 1,042
| Percent
Births to mothers younger than age 20 | 4.0 | 7.6 | 0.4 | 5.9 | 4.6 | 2.5 | 6.2
4th and higher-order births^5^ | 12.9 | 23.0 | 6.0 | 18.8 | 28.3 | 11.0 | 14.6
Births to unmarried mothers | 40.0 | 68.7 | 12.0 | 69.3 | 52.7 | 26.8 | 54.2
Mothers born in the 50 states or District of Columbia | 76.5 | 98.6 | 23.8 | 81.0 | 34.7 | 93.2 | 53.3
Educational attainment of mother:
High school diploma or higher | 88.7 | 82.0 | 95.1 | 88.6 | 77.9 | 93.8 | 77.9
Bachelor's degree or higher | 36.1 | 11.8 | 69.4 | 20.4 | 10.0 | 46.8 | 17.8
| Mean
Age of mother at first birth | 27.5 | 24.2 | 31.5 | 25.9 | 25.2 | 28.3 | 25.7

1 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic females are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

4 Male births per 1,000 female births.

5 Based on live-birth order.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality date file.

Table 12 Selected demographic characteristics of births, by Hispanic origin of mother: United States, 2023

[Mean age at first birth is the arithmetic average of the age of mothers at the time of birth, computed directly from the frequency of first births by age of mother]

Characteristic | Total^1^ | Central and South American | Cuban | Dominican | Mexican | Puerto Rican | Other and unknown Hispanic
| Number
Births | 945,200 | 208,618 | 30,001 | 33,575 | 508,127 | 66,203 | 98,676
| Ratio
Sex ratio^2^ | 1,042 | 1,047 | 1,052 | 1,064 | 1,036 | 1,046 | 1,044
| Percent
Births to mothers younger than age 20 | 6.2 | 7.0 | 2.1 | 3.6 | 6.3 | 5.8 | 6.3
4th and higher-order births^3^ | 14.6 | 13.1 | 4.8 | 9.0 | 16.5 | 13.5 | 13.9
Mothers born in the 50 states or District of Columbia | 53.3 | 16.4 | 35.3 | 31.0 | 64.9 | 72.9 | 71.9
Educational attainment of mother:
High school diploma or higher | 77.9 | 62.0 | 90.6 | 87.0 | 80.7 | 88.0 | 83.5
Bachelor's degree or higher | 17.8 | 18.1 | 33.3 | 25.3 | 15.4 | 20.5 | 20.8
| Mean
Age of mother at first birth | 25.7 | 26.0 | 28.2 | 26.9 | 25.2 | 25.9 | 26.1

1 Includes origin not stated.

2 Male births per 1,000 female births.

3 Based on live-birth order.

NOTES: In this table, Hispanic women are classified only by place of origin; non-Hispanic women are not shown. Other and unknown Hispanic includes origins not otherwise classified, including Spaniard. See Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Among race and Hispanic-origin groups, the number of births declined 1% for Asian, 3% for White, and 4% for both American Indian and Alaska Native and Black women from 2022 to 2023, and rose 1% for Hispanic women (Tables 1, 3, and 6). The change in the number of births for Native Hawaiian and Other Pacific Islander women was not significant. Among specified Hispanic groups, births rose 14% for Cuban women and declined less than 1% for Mexican and 4% for Puerto Rican women (Tables 4 and 7) (15). The changes in the number of births for Central and South American and Dominican women were not significant.

Table 13 Selected medical and health characteristics of births, by race and Hispanic origin of mother: United States, 2023

Characteristic | All races and origins^2^ | Non-Hispanic, single race^1^
Characteristic | All races and origins^2^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian and Pacific Islander | White | Hispanic^3^
Mother | Percent
Prenatal care initiation:
First trimester | 76.1 | 64.5 | 81.1 | 66.3 | 48.5 | 82.4 | 68.9
Late or no care^4^ | 7.0 | 12.6 | 4.9 | 10.4 | 22.4 | 4.7 | 9.7
Smoked during pregnancy | 3.0 | 9.6 | 0.2 | 2.7 | 1.7 | 4.4 | 0.8
Pregnancy resulted from infertility treatment | 2.5 | 0.6 | 5.3 | 1.1 | 0.6 | 3.3 | 1.0
Mother received WIC^5^ food for herself during this pregnancy | 31.6 | 47.5 | 16.9 | 46.5 | 34.8 | 19.5 | 49.7
Diabetes:
Prepregnancy (diagnosis before this pregnancy) | 1.2 | 3.3 | 1.5 | 1.7 | 2.3 | 1.0 | 1.4
Gestational (diagnosis in this pregnancy) | 8.3 | 12.8 | 15.8 | 6.7 | 10.7 | 7.5 | 8.7
Overweight or obese (BMI^6^ of 25.0 or over) | 59.7 | 70.6 | 40.7 | 68.8 | 77.6 | 55.7 | 66.8
Induction of labor | 33.2 | 34.7 | 30.5 | 31.4 | 25.8 | 36.2 | 29.0
Certified nurse midwife delivery | 11.4 | 19.7 | 9.4 | 10.1 | 11.1 | 12.1 | 10.7
Home births | 1.5 | 0.9 | 0.4 | 0.8 | 0.9 | 2.3 | 0.5
Cesarean delivery (total) | 32.3 | 29.9 | 34.2 | 37.0 | 32.5 | 31.1 | 32.0
Low-risk^7^ | 26.6 | 23.6 | 30.1 | 30.8 | 28.9 | 25.6 | 25.9
Source of payment for the delivery:
Medicaid | 41.5 | 65.3 | 22.1 | 64.5 | 59.5 | 27.6 | 58.8
Private | 51.0 | 23.7 | 72.4 | 30.4 | 28.0 | 65.1 | 31.5
Self-pay | 4.4 | 1.8 | 2.7 | 2.3 | 6.6 | 4.0 | 6.7
Other^8^ | 3.2 | 9.2 | 2.8 | 2.8 | 5.9 | 3.3 | 3.0
Infant was being breastfed at discharge^9^ | 84.8 | 77.0 | 89.8 | 75.9 | 78.8 | 86.0 | 87.1
Infant
Gestational age:
Preterm^10^ | 10.41 | 12.23 | 9.08 | 14.65 | 12.52 | 9.44 | 10.14
Early preterm^11^ | 2.76 | 3.02 | 2.29 | 4.86 | 3.24 | 2.28 | 2.62
Late preterm^12^ | 7.64 | 9.21 | 6.79 | 9.79 | 9.28 | 7.16 | 7.52
Birthweight^13^:
Very low birthweight^14^ | 1.36 | 1.38 | 1.14 | 2.86 | 1.55 | 1.00 | 1.26
Low birthweight^15^ | 8.58 | 8.65 | 9.44 | 14.80 | 9.34 | 7.04 | 7.92
Twin births^16^ | 30.70 | 27.19 | 24.57 | 41.40 | 26.69 | 31.70 | 24.28
Triplet and higher-order births^17^ | 73.78 | * | 50.99 | 108.85 | * | 76.10 | 56.60

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

4 Prenatal care beginning in the third trimester.

5 Special Supplemental Nutrition Program for Women, Infants, and Children.

6 Body mass index.

7 Rate is number of singleton, term (37 weeks of gestation or more based on the obstetric estimate), cephalic (head first), cesarean deliveries to women having a first birth per 100 women delivering singleton, term, cephalic births.

8 Includes Indian Health Service, CHAMPUS or TRICARE, other government (federal, state, or local), or charity.

9 Excludes data for California, which did not report if infant was being breastfed at discharge.

10 Born before 37 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

11 Born before 34 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

12 Born between 34 and 36 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

13 Equivalents of gram weights in pounds are shown in the User Guide; see reference 9 in this report.

14 Less than 1,500 grams (3 lb 4 oz).

15 Less than 2,500 grams (5 lb 8 oz).

16 Live births in twin deliveries per 1,000 live births.

17 Live births in triplet and other higher-order multiple deliveries per 100,000 live births.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 16 Trimester prenatal care began, by age and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin of mother and trimester care began | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54
All races and origins^1^ | Percent
First trimester | 76.1 | 57.6 | 69.7 | 76.4 | 80.1 | 79.5 | 75.8
Second trimester | 16.9 | 27.6 | 21.1 | 16.8 | 14.3 | 14.8 | 17.5
Late or no care | 7.0 | 14.8 | 9.2 | 6.8 | 5.6 | 5.7 | 6.6
Third trimester | 4.7 | 9.9 | 6.3 | 4.6 | 3.8 | 3.8 | 4.5
No care | 2.3 | 4.9 | 2.9 | 2.2 | 1.9 | 1.9 | 2.1
| Number
Total | 3,596,017 | 142,743 | 616,970 | 986,567 | 1,098,052 | 604,631 | 147,054
Not stated | 67,433 | 3,354 | 12,536 | 18,170 | 19,340 | 11,032 | 3,001
Non-Hispanic, single race^2^ | Percent
Black:
First trimester | 66.3 | 53.8 | 63.8 | 66.5 | 68.9 | 69.1 | 67.9
Second trimester | 23.3 | 30.7 | 25.0 | 23.2 | 21.4 | 21.7 | 22.8
Late or no care | 10.4 | 15.5 | 11.2 | 10.3 | 9.7 | 9.2 | 9.3
Third trimester | 6.6 | 9.8 | 7.0 | 6.4 | 6.1 | 5.9 | 6.3
No care | 3.8 | 5.7 | 4.2 | 3.9 | 3.5 | 3.3 | 3.0
| Number
Total | 491,494 | 28,900 | 103,077 | 131,705 | 131,500 | 74,492 | 21,820
Not stated | 11,749 | 700 | 2,499 | 3,215 | 3,036 | 1,788 | 511
White: | Percent
First trimester | 82.4 | 68.2 | 76.7 | 82.5 | 85.1 | 84.3 | 80.8
Second trimester | 12.9 | 22.4 | 17.0 | 12.9 | 11.0 | 11.5 | 13.9
Late or no care | 4.7 | 9.4 | 6.3 | 4.6 | 3.9 | 4.2 | 5.4
Third trimester | 3.2 | 6.5 | 4.5 | 3.2 | 2.6 | 2.8 | 3.5
No care | 1.5 | 2.9 | 1.8 | 1.4 | 1.3 | 1.4 | 1.8
| Number
Total | 1,787,051 | 45,273 | 263,760 | 500,910 | 595,741 | 314,198 | 67,169
Not stated | 24,638 | 690 | 3,859 | 6,505 | 7,915 | 4,493 | 1,176
Hispanic^3^ | Percent
First trimester | 68.9 | 51.5 | 64.2 | 70.5 | 73.2 | 72.5 | 69.3
Second trimester | 21.5 | 30.0 | 24.0 | 20.6 | 19.0 | 19.8 | 22.5
Late or no care | 9.7 | 18.5 | 11.8 | 9.0 | 7.8 | 7.7 | 8.3
Third trimester | 6.6 | 12.4 | 8.2 | 6.2 | 5.4 | 5.2 | 5.8
No care | 3.0 | 6.1 | 3.6 | 2.8 | 2.4 | 2.4 | 2.5
| Number
Total | 945,200 | 58,714 | 207,702 | 270,317 | 240,489 | 131,623 | 36,355
Not stated | 21,540 | 1,684 | 4,994 | 6,175 | 5,183 | 2,734 | 770

1 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

2 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

3 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Heatlh Statistics, National Vital Statistics System, natality data file.

Table 17 Births, by method of delivery: United States, 2010–2023, and race and Hispanic origin of mother: United States, 2016–2023

Race and Hispanic origin and year | All births | Vaginal | | Cesarean | | | Not stated | Cesarean | | | Vaginal birth after previous cesarean delivery^7^
Race and Hispanic origin and year | All births | Total^1^ | After previous cesarean | Total^2^ | Primary | Low-risk^3^ | Not stated | Total^4^ | Primary^5^ | Low-risk^6^ | Vaginal birth after previous cesarean delivery^7^
All races and origins^8^ | Number | | | | | | | Percent
2023 | 3,596,017 | 2,431,500 | 83,392 | 1,161,896 | 692,747 | 323,302 | 2,621 | 32.3 | 22.8 | 26.6 | 15.1
2022 | 3,667,758 | 2,486,963 | 82,284 | 1,178,066 | 696,495 | 320,490 | 2,729 | 32.1 | 22.5 | 26.3 | 14.6
2021 | 3,664,292 | 2,486,856 | 79,555 | 1,174,545 | 691,550 | 316,349 | 2,891 | 32.1 | 22.3 | 26.3 | 14.2
2020 | 3,613,647 | 2,462,904 | 77,776 | 1,148,692 | 666,599 | 310,303 | 2,051 | 31.8 | 21.9 | 25.9 | 13.9
2019 | 3,747,540 | 2,558,882 | 80,140 | 1,186,397 | 683,900 | 314,016 | 2,261 | 31.7 | 21.6 | 25.6 | 13.8
2018 | 3,791,712 | 2,581,992 | 78,842 | 1,208,176 | 693,276 | 319,022 | 1,544 | 31.9 | 21.7 | 25.9 | 13.3
2017 | 3,855,500 | 2,621,010 | 76,301 | 1,232,339 | 710,963 | 325,086 | 2,151 | 32.0 | 21.9 | 26.0 | 12.8
2016 | 3,945,875 | 2,684,803 | 75,244 | 1,258,581 | 728,500 | 329,614 | 2,491 | 31.9 | 21.8 | 25.7 | 12.4
2015 | 3,978,497 | 2,703,504 | --- | 1,272,503 | --- | 331,982 | 2,490 | 32.0 | --- | 25.8 | ---
2014 | 3,988,076 | 2,699,951 | --- | 1,284,551 | --- | 337,086 | 3,574 | 32.2 | --- | 26.0 | ---
2013 | 3,932,181 | 2,642,892 | --- | 1,284,339 | --- | 344,405 | 4,950 | 32.7 | --- | 26.8 | ---
2012 | 3,952,841 | 2,650,744 | --- | 1,296,070 | --- | 355,942 | 6,027 | 32.8 | --- | 27.2 | ---
2011 | 3,953,590 | 2,651,428 | --- | 1,293,267 | --- | 359,669 | 8,895 | 32.8 | --- | 27.2 | ---
2010 | 3,999,386 | 2,680,947 | --- | 1,309,182 | --- | 368,523 | 9,257 | 32.8 | --- | 27.5 | ---
Non-Hispanic, single race^9^
Black:
2023 | 491,494 | 309,644 | 13,304 | 181,602 | 105,603 | 44,791 | 248 | 37.0 | 26.3 | 30.8 | 14.9
2022 | 511,439 | 323,076 | 13,430 | 188,132 | 109,189 | 46,477 | 231 | 36.8 | 26.1 | 30.8 | 14.6
2021 | 517,889 | 327,049 | 12,687 | 190,500 | 111,166 | 47,977 | 340 | 36.8 | 26.2 | 31.2 | 13.8
2020 | 529,811 | 337,264 | 12,911 | 192,338 | 110,612 | 48,448 | 209 | 36.3 | 25.5 | 30.6 | 13.7
2019 | 548,075 | 351,191 | 13,159 | 196,672 | 113,001 | 48,481 | 212 | 35.9 | 25.1 | 30.0 | 13.6
2018 | 552,029 | 352,750 | 12,702 | 199,117 | 114,150 | 49,481 | 162 | 36.1 | 25.2 | 30.3 | 13.0
2017 | 560,715 | 358,467 | 12,457 | 201,991 | 117,054 | 50,217 | 257 | 36.0 | 25.3 | 30.4 | 12.8
2016 | 558,622 | 357,859 | 11,763 | 200,460 | 117,410 | 50,287 | 303 | 35.9 | 25.4 | 30.3 | 12.4
White:
2023 | 1,787,051 | 1,229,961 | 38,631 | 555,949 | 340,939 | 159,184 | 1,141 | 31.1 | 22.3 | 25.6 | 15.3
2022 | 1,840,739 | 1,268,223 | 38,353 | 571,371 | 347,632 | 160,403 | 1,145 | 31.1 | 22.1 | 25.3 | 14.7
2021 | 1,887,656 | 1,301,124 | 38,908 | 585,346 | 353,971 | 161,487 | 1,186 | 31.0 | 21.9 | 25.2 | 14.4
2020 | 1,843,432 | 1,275,917 | 36,967 | 566,811 | 339,770 | 157,635 | 704 | 30.8 | 21.5 | 24.9 | 14.0
2019 | 1,915,912 | 1,327,934 | 38,442 | 587,111 | 348,616 | 160,622 | 867 | 30.7 | 21.3 | 24.7 | 13.9
2018 | 1,956,413 | 1,353,424 | 38,345 | 602,361 | 356,796 | 164,087 | 628 | 30.8 | 21.4 | 24.9 | 13.5
2017 | 1,992,461 | 1,375,702 | 37,295 | 615,830 | 366,505 | 167,434 | 929 | 30.9 | 21.5 | 24.9 | 13.0
2016 | 2,056,332 | 1,419,788 | 37,442 | 635,588 | 379,240 | 172,006 | 956 | 30.9 | 21.5 | 24.7 | 12.8
Hispanic^10^ | Number | | | | | | | Percent
2023 | 945,200 | 642,354 | 22,688 | 302,522 | 170,279 | 80,106 | 324 | 32.0 | 21.6 | 25.9 | 14.7
2022 | 937,421 | 640,248 | 21,880 | 296,706 | 165,122 | 75,640 | 467 | 31.7 | 21.1 | 25.6 | 14.3
2021 | 885,916 | 605,819 | 19,485 | 279,607 | 154,162 | 70,443 | 490 | 31.6 | 20.8 | 25.5 | 13.5
2020 | 866,713 | 594,463 | 19,469 | 271,865 | 145,786 | 67,517 | 385 | 31.4 | 20.2 | 25.1 | 13.4
2019 | 886,467 | 608,445 | 19,612 | 277,578 | 147,597 | 66,705 | 444 | 31.3 | 20.1 | 24.8 | 13.1
2018 | 886,210 | 605,674 | 19,371 | 280,386 | 147,149 | 67,040 | 150 | 31.6 | 20.1 | 25.4 | 12.7
2017 | 898,764 | 613,101 | 18,423 | 285,379 | 150,592 | 67,860 | 284 | 31.8 | 20.2 | 25.6 | 12.0
2016 | 918,447 | 627,095 | 17,847 | 290,832 | 153,462 | 67,278 | 520 | 31.7 | 20.1 | 25.1 | 11.5

--- Comparable data not available for the 50 states and District of Columbia for 2010–2015 because not all reporting areas had adopted the 2003 U.S. Certificate of Live Birth.

1 Includes unknown type of vaginal delivery; see Technical Notes in this report.

2 Includes unknown type of cesarean delivery; see Technical Notes.

3 Singleton, term (37 completed weeks of gestation or more based on the obstetric estimate), cephalic (head first), cesarean deliveries to women having a first birth.

4 Percentage of all live births delivered by cesarean.

5 Rate is number of births to women having a cesarean delivery per 100 births to women without a previous cesarean.

6 Rate is number of singleton, term (37 completed weeks of gestation or more based on the obstetric estimate), cephalic, cesarean deliveries to women having a first birth per 100 women delivering singleton, term, cephalic, first births.

7 Rate is the number of births to women having a vaginal delivery per 100 births to women with a previous cesarean delivery.

8 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

9 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

10 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 14 Selected medical and health characteristics of births, by Hispanic origin of mother: United States, 2023

Characteristic | Total | Central and South American | Cuban | Dominican | Mexican | Puerto Rican | Other and unknown Hispanic
Mother | Percent
Prenatal care initiation:
First trimester | 68.9 | 58.8 | 71.3 | 71.3 | 71.0 | 75.8 | 73.0
Late or no care^1^ | 9.7 | 14.2 | 8.4 | 9.1 | 8.7 | 6.3 | 7.9
Smoked during pregnancy | 0.8 | 0.2 | 0.9 | 0.4 | 0.7 | 2.5 | 1.1
Pregnancy resulted from infertility treatment | 1.0 | 1.0 | 1.6 | 1.7 | 0.8 | 1.6 | 1.2
Mother received WIC^2^ food for herself during this pregnancy | 49.7 | 52.0 | 47.6 | 52.9 | 49.5 | 46.0 | 47.6
Diabetes:
Prepregnancy (diagnosis before this pregnancy) | 1.4 | 1.0 | 0.8 | 1.4 | 1.6 | 1.5 | 1.3
Gestational (diagnosis during this pregnancy) | 8.7 | 7.6 | 7.6 | 8.4 | 9.4 | 8.4 | 8.4
Overweight or obese (BMI^3^ of 25.0 or over) | 66.8 | 62.0 | 57.1 | 65.2 | 69.6 | 65.5 | 66.5
Induction of labor | 29.0 | 27.0 | 25.7 | 30.3 | 29.2 | 32.9 | 30.4
Certified nurse midwife delivery | 10.7 | 11.7 | 7.5 | 10.3 | 10.0 | 13.8 | 10.8
Home births | 0.5 | 0.5 | 0.6 | 0.4 | 0.5 | 0.9 | 0.8
Cesarean delivery (total) | 32.0 | 30.6 | 44.7 | 41.1 | 30.9 | 33.8 | 32.8
Low-risk^4^ | 25.9 | 24.6 | 37.2 | 30.8 | 24.8 | 28.3 | 26.2
Source of payment for the delivery:
Medicaid | 58.8 | 60.1 | 54.0 | 63.8 | 58.8 | 56.7 | 57.2
Private | 31.5 | 25.1 | 41.5 | 30.6 | 31.9 | 37.8 | 35.6
Self-pay | 6.7 | 11.8 | 2.4 | 2.9 | 6.3 | 1.5 | 4.1
Other^5^ | 3.0 | 3.0 | 2.1 | 2.7 | 2.9 | 4.1 | 3.1
Infant was being breastfed at discharge^6^ | 87.1 | 88.5 | 90.1 | 89.1 | 86.7 | 84.1 | 86.0
Infant
Gestational age:
Preterm^7^ | 10.14 | 9.55 | 9.76 | 10.24 | 10.07 | 11.81 | 10.67
Early preterm^8^ | 2.62 | 2.34 | 2.57 | 2.91 | 2.59 | 3.36 | 2.75
Late preterm^9^ | 7.52 | 7.22 | 7.20 | 7.33 | 7.47 | 8.44 | 7.92
Birthweight^10^:
Very low birthweight^11^ | 1.26 | 1.10 | 1.30 | 1.60 | 1.23 | 1.73 | 1.33
Low birthweight^12^ | 7.92 | 7.36 | 7.21 | 9.05 | 7.69 | 10.42 | 8.49
Twin births^13^ | 24.28 | 20.72 | 28.43 | 28.98 | 23.87 | 31.36 | 26.35
Triplet and higher-order births^14^ | 56.60 | 36.43 | 63.33 | 139.99 | 51.17 | 123.86 | 51.68

1 Late care is prenatal care beginning in the third trimester.

2 Special Supplemental Nutrition Program for Women, Infants, and Children.

3 Body mass index.

4 Rate is number of singleton, term (37 weeks of gestation or more based on the obstetric estimate), cephalic (head first), cesarean deliveries to women having a first birth per 100 women delivering singleton, term, cephalic births.

5 Includes Indian Health Service, CHAMPUS or TRICARE, other government (federal, state, or local), or charity.

6 Excludes data for California, which did not report if infant was being breastfed at discharge.

7 Born before 37 completed weeks of gestation, based on the obstetric estimate; see Technical Notes in this report.

8 Born before 34 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

9 Born between 34 and 36 completed weeks of gestation, based on the obstetric estimate; see Technical Notes.

10 Equivalents of gram weights in pounds are shown in the User Guide (10).

11 Less than 1,500 grams (3 lb 4 oz).

12 Less than 2,500 grams (5 lb 8 oz).

13 Live births in twin deliveries per 1,000 live births.

14 Live births in triplet and other higher-order multiple deliveries per 100,000 live births.

NOTES: In this table, Hispanic women are classified only by place of origin; non-Hispanic women are not shown. Other and unknown Hispanic includes origins not otherwise classified, including Spaniard. See Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statitics System, natality data file.

Table 18 Births, by method of delivery and by age and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin and age of mother | All births | Vaginal | | Cesarean | | | Not stated | Cesarean | | | Vaginal birth after previous cesarean delivery^7^
Race and Hispanic origin and age of mother | All births | Total^1^ | After previous cesarean | Total^2^ | Primary | Low-risk^3^ | Not stated | Total^4^ | Primary^5^ | Low-risk^6^ | Vaginal birth after previous cesarean delivery^7^
All races and origins^8^ | Number | | | | | | | Percent
All ages | 3,596,017 | 2,431,500 | 83,392 | 1,161,896 | 692,747 | 323,302 | 2,621 | 32.3 | 22.8 | 26.6 | 15.1
Younger than 20 | 142,743 | 115,773 | 461 | 26,899 | 24,547 | 16,213 | 71 | 18.9 | 17.6 | 15.1 | 16.6
20–24 | 616,970 | 463,138 | 7,762 | 153,321 | 111,551 | 64,831 | 511 | 24.9 | 19.7 | 20.8 | 15.7
25–29 | 986,567 | 691,906 | 21,656 | 293,915 | 183,118 | 91,059 | 746 | 29.8 | 21.5 | 26.1 | 16.4
30–34 | 1,098,052 | 723,121 | 30,303 | 374,204 | 211,125 | 91,376 | 727 | 34.1 | 23.4 | 30.3 | 15.7
35–39 | 604,631 | 361,303 | 18,809 | 242,886 | 124,716 | 46,531 | 442 | 40.2 | 26.7 | 39.1 | 13.8
40–54 | 147,054 | 76,259 | 4,401 | 70,671 | 37,690 | 13,292 | 124 | 48.1 | 34.4 | 53.6 | 11.8
Non-Hispanic, single race^9^
Black:
All ages | 491,494 | 309,644 | 13,304 | 181,602 | 105,603 | 44,791 | 248 | 37.0 | 26.3 | 25.6 | 14.9
Younger than 20 | 28,900 | 22,803 | 93 | 6,085 | 5,571 | 3,683 | 12 | 21.1 | 19.7 | 15.0 | 15.5
20–24 | 103,077 | 73,560 | 1,514 | 29,465 | 21,559 | 12,250 | 52 | 28.6 | 23.1 | 19.4 | 16.1
25–29 | 131,705 | 85,611 | 3,715 | 46,023 | 26,891 | 12,096 | 71 | 35.0 | 24.8 | 23.9 | 16.3
30–34 | 131,500 | 78,311 | 4,650 | 53,121 | 27,633 | 9,788 | 68 | 40.4 | 27.3 | 28.3 | 15.5
35–39 | 74,492 | 39,556 | 2,707 | 34,900 | 17,421 | 5,177 | 36 | 46.9 | 32.1 | 36.8 | 13.4
40–54 | 21,820 | 9,803 | 625 | 12,008 | 6,528 | 1,797 | 9 | 55.1 | 41.7 | 51.2 | 10.3
White:
All ages | 1,787,051 | 1,229,961 | 38,631 | 555,949 | 340,939 | 159,184 | 1,141 | 31.1 | 22.3 | 25.6 | 15.3
Younger than 20 | 45,273 | 36,463 | 108 | 8,785 | 8,094 | 5,172 | 25 | 19.4 | 18.2 | 15.0 | 13.8
20–24 | 263,760 | 200,109 | 2,609 | 63,439 | 46,938 | 26,455 | 212 | 24.1 | 19.2 | 19.4 | 13.7
25–29 | 500,910 | 358,788 | 9,301 | 141,806 | 93,264 | 46,365 | 316 | 28.3 | 21.1 | 23.9 | 16.1
30–34 | 595,741 | 403,191 | 15,091 | 192,211 | 113,211 | 49,980 | 339 | 32.3 | 22.6 | 28.3 | 16.1
35–39 | 314,198 | 194,947 | 9,444 | 119,056 | 62,800 | 24,565 | 195 | 37.9 | 25.3 | 36.8 | 14.4
40–54 | 67,169 | 36,463 | 2,078 | 30,652 | 16,632 | 6,647 | 54 | 45.7 | 32.6 | 51.2 | 12.9
Hispanic^10^
All ages | 945,200 | 642,354 | 22,688 | 302,522 | 170,279 | 80,106 | 324 | 32.0 | 21.6 | 25.9 | 14.7
Younger than 20 | 58,714 | 48,506 | 226 | 10,187 | 9,180 | 6,258 | 21 | 17.4 | 16.0 | 14.0 | 18.5
20–24 | 207,702 | 157,351 | 3,034 | 50,260 | 35,589 | 21,787 | 91 | 24.2 | 18.8 | 20.8 | 17.2
25–29 | 270,317 | 188,004 | 6,796 | 82,227 | 46,810 | 23,424 | 86 | 30.4 | 20.6 | 28.1 | 16.1
30–34 | 240,489 | 153,833 | 7,342 | 86,582 | 43,590 | 17,577 | 74 | 36.0 | 23.0 | 33.8 | 14.6
35–39 | 131,623 | 75,832 | 4,225 | 55,753 | 26,470 | 8,696 | 38 | 42.4 | 27.0 | 42.8 | 12.6
40–54 | 36,355 | 18,828 | 1,065 | 17,513 | 8,640 | 2,364 | 14 | 48.2 | 32.8 | 54.7 | 10.7

1 Includes unknown type of vaginal delivery; see Technical Notes in this report.

2 Includes unknown type of cesarean delivery; see Technical Notes.

3 Singleton, term (37 completed weeks of gestation or more based on the obstetric estimate), cephalic (head first), cesarean deliveries to women having a first birth.

4 Percentage of all live births delivered by cesarean.

5 Rate is the number of births to women having a cesarean delivery per 100 births to women without a previous cesarean.

6 Rate is the number of singleton, term (37 completed weeks of gestation or more based on the obstetric estimate), cephalic, cesarean deliveries to women having a first birth per 100 women delivering singleton, term, cephalic, first births.

7 Rate is the number of births to women having a vaginal delivery per 100 births to women with a previous cesarean delivery.

8 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

9 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

10 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

### Fertility rate

The general fertility rate (GFR) for the United States in 2023 was 54.5 births per 1,000 women ages 15–44, down 3% from 2022 (56.0) (Table 1). The GFR has generally declined since 2008, by an average 1% per year (12).

Among the race and Hispanic-origin groups, the GFR declined 2% for Hispanic, 3% for both Asian and White, 4% for Black, and 5% for American Indian and Alaska Native women from 2022 to 2023 (Table 1). The rate for Native Hawaiian and Other Pacific Islander women was essentially unchanged.

### Age of mother

Birth rates declined for females ages 15–19 and 25–44, rose for those ages 20–24, and were unchanged for ages 10–14 and 45–49 from 2022 to 2023 (Table 2, Figure 2).

Figure 2 Birth rate, by selected age of mother: United States, 1990–2023

NOTES: Rates for 2020 have been revised and may differ from those published in “Births: Final Data for 2020.” Rates are plotted on a logarithmic scale.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 2 is a line graph showing the birth rate by selected age of mother in the United States, 1990–2023.

Teenagers—The birth rate for females ages 15–19 in the United States in 2023 was 13.1 births per 1,000, down 4% from 2022 (13.6) and another record low (12,15,16). Since 2009, the teen birth rate has fallen to a new low each year. The rate for this group has declined 68% since 2007 (41.5), the most recent high, and 79% since the 1991 high (61.8). The number of births to teenagers ages 15–19 was 140,977 in 2023, down 2% from 2022 (143,789) (Table 3) (15).

The 2023 birth rate for teenagers ages 15–17 was 5.5 births per 1,000 females, down 2% from 2022 and a record low. The rate for those ages 18–19 was 24.6 births, down 5% from 2022 and another record low. Rates for these age groups have fallen 75% and 66%, respectively, since 2007, and by 86% and 74% since 1991. The birth rate for females ages 10–14 was unchanged in 2023 at 0.2 births per 1,000 females.

Among race and Hispanic-origin groups, birth rates for teenagers ages 15–19 declined for most groups, down 8% for White, 7% American Indian and Alaska Native, 5% for Black, and 2% for Hispanic females from 2022 to 2023. The change in rates for Asian and Native Hawaiian and Other Pacific Islander females was not significant.

Women in their 20s—The birth rate for women ages 20–24 was 57.7 births per 1,000 women in 2023, up less than 1% from 2022 (57.5), which was a record low (Table 2) (12,16). The rate for women in this age group declined steadily from 2006 to 2022. The number of births to women in their early 20s declined 3% from 2022 (Table 3) (15). The rate for women ages 25–29 was 91.0 births per 1,000 women, down 3% from 2022 (93.5). The rate for women in this age group has generally declined from 2008 to 2023 (12). The number of births to women ages 25–29 declined 3% from 2022 to 2023 (15).

Women in their 30s—The birth rate for women ages 30–34 was 94.3 births per 1,000 women in 2023, down 3% from 2022 (97.5); the rate has generally declined since 2017 by an average of 1% per year (Table 2). The 2023 rate for women ages 30–34 was higher than the rate for women ages 25–29 for the eighth consecutive year since reliable national records were available (1940) (12,16). The number of births to women ages 30–34 declined by 2% from 2022 to 2023 (Table 3) (15). The birth rate for women ages 35–39 was 54.3 births per 1,000 women in 2023, down 2% from 2022 (55.3) (Table 2). The number of births to women ages 35–39 was essentially unchanged in 2023 (15).

Women in their 40s—The birth rate for women ages 40–44 was 12.5 births per 1,000 women in 2023, down 1% from 2022 (12.6) (Table 2). The rate for this group has generally risen since 1985 (12,16). The number of births to women in their early 40s rose 2% from 2022 to 2023 (Table 3) (15). The birth rate for women ages 45–49 (includes births to women age 50 and older) was 1.1 in 2023, unchanged from 2022. The number of births to women age 45 and older was essentially unchanged from 2022 to 2023 (15).

Women age 50 and older—The birth rate for women ages 50–54 was 1.2 births per 10,000 women in 2023, unchanged from 2022. Because of the small number of births to women in this age group, the birth rate for women ages 50–54 is expressed per 10,000 women. For rates shown elsewhere in this report, births to women age 50 and older are included with births to women ages 45–49 when computing birth rates by age of mother (the denominator for the rate is women ages 45–49). A total of 1,217 births were to women age 50 and older in 2023, essentially unchanged from 1,230 in 2023 (Table 3) (15). The number of births to women in this age group has generally increased since 1997, when 144 births were reported (15).

### Live-birth order

The first-birth rate for the United States was 21.4 births per 1,000 females ages 15–44 in 2023, down 1% from 2022 (21.6) (see Tables 3 and 4 for the number of births and Table 5 for birth rates) (15). First-birth rates declined for females in their teens (3% for females ages 15–19) and early 30s (1% for women ages 30–34) and rose for women in their early 20s (2% for ages 20–24). The first-birth rate was essentially unchanged for females ages 10–14 (0.2), 25–29 (37.1), 35–39 (13.0), and women in their 40s (2.7 for ages 40–44 and 0.3 for ages 45–49) in 2023 (15).

#### Mean age of mother

In 2023, the mean age of mothers at first birth was 27.5 years, an increase from 27.4 in 2022 and another record high for the nation (Tables 11, 12, and III) (12,16). The mean age at first birth is the arithmetic average of the age of mothers at the time of birth and is computed directly from the frequency of first births by age of mother. The increase in the mean age in 2023 reflects the decline in the number of first births to females in their teens and early 20s and the concurrent rise in first births to women in their late 20s, 30s, and 40s (15).

Mean age at first birth increased for three race and Hispanic-origin groups in 2023, rising to 25.9 for Black, 28.3 for White, and 31.5 for Asian women (Table III). The average age at first birth for American Indian and Alaska Native (24.2), Native Hawaiian and Other Pacific Islander (25.2), and Hispanic (25.7) women was unchanged from 2022. Among the specified Hispanic groups, average age increased to 25.2 for Mexican and 25.9 for Puerto Rican women (Table 12) (15). The age at first birth for Central and South American and Cuban women declined in 2023 to 26.0 and 28.2, respectively; the age at first birth for Dominican women was essentially unchanged at 26.9.

### Total fertility rate

The total fertility rate (TFR) for the United States in 2023 was 1,621.0 births per 1,000 women, down 2% from 2022 (1,656.5) (Table 2). The TFR has generally declined since 2008 by an average of 2% per year. TFR estimates the number of births that a hypothetical group of 1,000 women would have over their lifetimes, based on age-specific birth rates in a given year. Because it is calculated from age-specific birth rates, TFR is age adjusted and can be compared for populations across time, population groups, and geographic areas.

Among race and Hispanic-origin groups, the TFR declined 1% for Hispanic, 2% for White, 3% for Asian, and 4% for both American Indian and Alaska Native and Black women from 2022 to 2023. The rate for Native Hawaiian and Other Pacific Islander women was essentially unchanged.

The TFR for the nation in 2023 remained below replacement, the level at which a given generation can exactly replace itself (generally considered to be 2,100 births per 1,000 women). The U.S. TFR has generally been below replacement since 1971 and has consistently been below replacement since 2008 (12,16). The TFR was below replacement for all race and Hispanic-origin groups in 2023 except for Native Hawaiian and Other Pacific Islander women (2,218.0 births) (Table 2).

### Births and birth rates by state

GFR, the number of births per 1,000 females ages 15–44, declined in 39 states and D.C. from 2022 to 2023. Decreases of 1%–2% were reported in 16 states (Alabama, Arizona, Arkansas, Georgia, Indiana, Iowa, Kentucky, Louisiana, Nebraska, New Jersey, New York, Ohio, Oklahoma, South Carolina, Texas, and Wisconsin), of 3%–4% in 16 states (Alaska, Colorado, Florida, Hawaii, Illinois, Massachusetts, Michigan, Minnesota, Missouri, New Mexico, North Carolina, Oregon, Pennsylvania, Utah, Virginia, and Washington) and D.C., and of 5% in 7 states (California, Delaware, Maine, Maryland, Nevada, Rhode Island, and Vermont). (See Tables 6 and 7 for the number of births and Table 8 for birth rates). GFRs were essentially unchanged in the remaining 11 states (15). Rates among the states ranged from 42.1 births per 1,000 females ages 15–44 in Vermont to 65.6 in South Dakota. Among the U.S. territories, GFR declined in Guam and Puerto Rico, rose in Northern Marianas, and was essentially unchanged in the U.S. Virgin Islands.

### Birth rates for teenagers by state

In 2023, the birth rate for teenagers ages 15–19 declined in 17 states (Arizona, California, Florida, Illinois, Indiana, Kansas, Kentucky, Maine, Michigan, Mississippi, Missouri, New Jersey, New Mexico, Ohio, Pennsylvania, Texas, and Wyoming), with declines ranging from 3% for Florida to 21% for Wyoming (Table 8). Rates were essentially unchanged in the remaining 33 states and D.C. (15). Rates among the states ranged from 4.6 births per 1,000 in New Hampshire to 24.9 in Mississippi. The wide range in state-specific teen birth rates is consistent with patterns observed in previous analyses (17,18). Teen birth rates were essentially unchanged for all of the territories except Northern Marianas, which rose. Rates among the territories ranged from 11.6 births per 1,000 teenagers in the U.S. Virgin Islands to 23.5 in Guam.

### Births to unmarried women

The birth rate for unmarried women was 36.4 births per 1,000 unmarried females ages 15–44 in 2023, down 2% from 2022 (37.2) (Table 10). The 2023 nonmarital birth rate was 30% lower than the peak of 51.8 in 2007 and 2008 (12). (See Technical Notes for a description of the adjustments to calculations of rates by marital status beginning with 2017 data).

The birth rate for married women declined 3% in 2023 to 81.6 per 1,000 married females ages 15–44 from 84.2 in 2022. The marital birth rate declined 4% over 2005–2010 but rose 6% from 2010 to 2016 before declining 6% through 2020 (12).

The percentage of all births to unmarried women was 40.0% in 2023, up less than 1% from 2022 (39.8%) (Table 9) (15). The percentage of all births to unmarried women peaked in 2009 at 41.0% (12,15).

The percentage of nonmarital births in 2023 decreased from 2022 for Asian (12.0% in 2023) and White (26.8%) women, increased for Hispanic women (54.2%), and was essentially unchanged for American Indian and Alaska Native (68.7%), Black (69.3%), and Native Hawaiian and Other Pacific Islander (52.75%) women. The number of nonmarital births declined by 1% from 2022 (1,461,305) to 2023 (1,440,031) (15).

Nonmarital birth rates declined 3% for teenagers ages 15–19 from 2022 to 2023 (to 12.3 per 1,000 unmarried females in 2023) (Table 10). The rate for females ages 15–17 declined 2% to an all-time low (5.5), and the rate for teenagers 18–19 declined 4% to 22.7. Rates also declined for women ages 25–29 (57.4) and ages 30–34 (57.5). Conversely, the nonmarital birth rate increased 1% for women ages 20–24 (44.6) and 2% for women ages 40–44 (11.8). The rate was unchanged for women ages 35–39, remaining at a historic peak of 38.8.

In 2023, the percentages of unmarried births ranged from about one in five births in Utah (21.3%) to more than one in two births in Louisiana (55.5%), Mississippi (54.9%), and New Mexico (52.7%) (Table IV).

## Cigarette Smoking Before and During Pregnancy (Tables 13–15)

Of the women who gave birth in 2023, 3.0% reported smoking cigarettes (tobacco only) at any time while pregnant, a 19% decline from 2022 (3.7%) and down 58% from 2016 (7.2%) (Table 15) (13,15). A recent report describes trends in cigarette smoking for 2016 through 2021 (19). Cigarette smoking was most common earlier in pregnancy: 2.9% of women smoked in their first trimester, 2.5% in their second, and 2.4% in their third. Of the 3.8% of women who reported smoking in the 3 months before becoming pregnant, 22.3% quit smoking before pregnancy.

Table 15 Mothers who smoked for the 3 months before pregnancy and anytime during pregnancy, and those who quit before and during pregnancy, by age and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin and tobacco use | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54
All races and origins^1^ | Percent
3 months before pregnancy | 3.8 | 2.9 | 4.3 | 4.0 | 3.7 | 3.4 | 3.3
Anytime during pregnancy | 3.0 | 2.2 | 3.3 | 3.2 | 2.9 | 2.8 | 2.7
First trimester | 2.9 | 2.1 | 3.2 | 3.1 | 2.9 | 2.7 | 2.6
Second trimester | 2.5 | 1.7 | 2.7 | 2.7 | 2.5 | 2.4 | 2.4
Third trimester | 2.4 | 1.6 | 2.6 | 2.5 | 2.4 | 2.3 | 2.3
Quit before pregnancy^2^ | 22.3 | 25.6 | 24.6 | 23.1 | 21.2 | 20.0 | 19.6
Quit during pregnancy^3^ | 19.3 | 27.8 | 22.8 | 19.6 | 17.6 | 16.9 | 16.1
Non-Hispanic, single race^4^
Black:
3 months before pregnancy | 3.4 | 1.2 | 2.2 | 3.5 | 4.3 | 4.2 | 3.5
Anytime during pregnancy | 2.7 | 0.9 | 1.7 | 2.7 | 3.5 | 3.5 | 3.0
First trimester | 2.6 | 0.9 | 1.6 | 2.7 | 3.4 | 3.4 | 2.9
Second trimester | 2.2 | 0.7 | 1.3 | 2.2 | 2.9 | 3.0 | 2.5
Third trimester | 2.1 | 0.6 | 1.2 | 2.1 | 2.7 | 2.7 | 2.3
Quit before pregnancy^2^ | 22.4 | 25.1 | 26.7 | 23.8 | 21.5 | 19.3 | 19.1
Quit during pregnancy^3^ | 23.0 | 30.3 | 27.9 | 23.8 | 22.1 | 19.7 | 22.5
White:
3 months before pregnancy | 5.5 | 6.2 | 7.5 | 5.8 | 4.8 | 4.6 | 4.9
Anytime during pregnancy | 4.4 | 5.0 | 6.0 | 4.6 | 3.9 | 3.8 | 4.2
First trimester | 4.3 | 4.9 | 5.8 | 4.5 | 3.8 | 3.7 | 4.1
Second trimester | 3.8 | 4.0 | 5.0 | 4.0 | 3.4 | 3.3 | 3.7
Third trimester | 3.6 | 3.7 | 4.7 | 3.8 | 3.3 | 3.2 | 3.6
Quit before pregnancy^2^ | 20.5 | 22.5 | 22.2 | 21.4 | 19.5 | 18.4 | 17.4
Quit during pregnancy^3^ | 17.6 | 25.3 | 20.9 | 18.0 | 15.9 | 15.0 | 13.4
Hispanic^5^
3 months before pregnancy | 1.2 | 0.8 | 1.1 | 1.2 | 1.3 | 1.2 | 1.0
Anytime during pregnancy | 0.8 | 0.5 | 0.7 | 0.8 | 0.9 | 0.9 | 0.7
First trimester | 0.7 | 0.5 | 0.7 | 0.7 | 0.9 | 0.8 | 0.7
Second trimester | 0.6 | 0.3 | 0.5 | 0.6 | 0.7 | 0.7 | 0.6
Third trimester | 0.5 | 0.3 | 0.5 | 0.5 | 0.7 | 0.6 | 0.5
Quit before pregnancy^2^ | 36.7 | 42.4 | 40.4 | 38.1 | 34.6 | 32.1 | 34.1
Quit during pregnancy^3^ | 28.7 | 36.1 | 32.4 | 29.0 | 26.2 | 26.9 | 25.1
All races and origins^1^ | Number
Total | 3,596,017 | 142,743 | 616,970 | 986,567 | 1,098,052 | 604,631 | 147,054
Not stated 3 months before pregnancy | 13,649 | 727 | 2,761 | 3,650 | 3,780 | 2,111 | 620
Not stated during pregnancy | 13,419 | 698 | 2,670 | 3,603 | 3,753 | 2,088 | 607
Quit before pregnancy^2^:
Smoked before pregnancy | 135,314 | 4,049 | 26,404 | 39,611 | 39,948 | 20,495 | 4,807
Unknown if quit | 240 | 5 | 39 | 72 | 85 | 30 | 9
Quit during pregnancy^3^:
Smoked before pregnancy | 107,763 | 3,151 | 20,453 | 31,181 | 32,201 | 16,796 | 3,981
Unknown if quit | 175 | 3 | 26 | 51 | 59 | 26 | 10
Non-Hispanic, single race^4^
Black:
Total | 491,494 | 28,900 | 103,077 | 131,705 | 131,500 | 74,492 | 21,820
Not stated 3 months before pregnancy | 2,017 | 117 | 438 | 502 | 594 | 280 | 86
Not stated during pregnancy | 1,985 | 112 | 426 | 494 | 586 | 280 | 87
Quit before pregnancy^2^:
Smoked before pregnancy | 16,583 | 332 | 2,255 | 4,567 | 5,575 | 3,087 | 767
Unknown if quit | 26 | 1 | 2 | 5 | 11 | 3 | 4
Quit during pregnancy^3^:
Smoked before pregnancy | 13,358 | 264 | 1,717 | 3,605 | 4,542 | 2,587 | 643
Unknown if quit | 35 | – | 3 | 11 | 12 | 7 | 2
White:
Total | 1,787,051 | 45,273 | 263,760 | 500,910 | 595,741 | 314,198 | 67,169
Not stated 3 months before pregnancy | 5,920 | 281 | 1,316 | 1,609 | 1,595 | 883 | 236
Not stated during pregnancy | 5,789 | 267 | 1,265 | 1,590 | 1,572 | 872 | 223
Quit before pregnancy^2^:
Smoked before pregnancy | 97,328 | 2,800 | 19,689 | 28,846 | 28,351 | 14,337 | 3,305
Unknown if quit | 127 | 4 | 20 | 41 | 40 | 21 | 1
Quit during pregnancy^3^:
Smoked before pregnancy | 78,993 | 2,254 | 15,688 | 23,134 | 23,221 | 11,902 | 2,794
Unknown if quit | 78 | – | 17 | 23 | 25 | 9 | 4
Hispanic^5^
Total | 945,200 | 58,714 | 207,702 | 270,317 | 240,489 | 131,623 | 36,355
Not stated 3 months before pregnancy | 2,492 | 189 | 542 | 719 | 614 | 323 | 105
Not stated during pregnancy | 2,442 | 184 | 528 | 702 | 608 | 314 | 106
Quit before pregnancy^2^:
Smoked before pregnancy | 11,008 | 472 | 2,285 | 3,140 | 3,130 | 1,609 | 372
Unknown if quit | 34 | – | 10 | 9 | 12 | 1 | 2
Quit during pregnancy^3^:
Smoked before pregnancy | 7,291 | 291 | 1,420 | 2,033 | 2,138 | 1,152 | 257
Unknown if quit | 27 | – | 2 | 9 | 9 | 5 | 2

– Quantity zero.

1 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

2 Births to women not reporting smoking during pregnancy per 100 women who smoked in the 3 months before pregnancy; see Technical Notes in this report.

3 Births to women not reporting smoking in the third trimester of pregnancy per 100 women who smoked in either the first or second trimester; see Technical Notes.

4 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

5 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

By race and Hispanic origin, 4.4% of White women reported smoking any time during pregnancy, down 19% from 2022; 2.7% of Black women reported smoking any time during pregnancy, down 13%; and 0.8% of Hispanic women reported smoking during pregnancy, down 20% from 2022. See Tables 13 and 14 for 2023 smoking levels among other race and Hispanic-origin groups. Rates of quitting smoking before pregnancy also varied by race and Hispanic origin: 20.5% of White, 22.4% of Black, and 36.7% of Hispanic women who smoked during the 3 months before pregnancy did not smoke while pregnant.

By maternal age, smoking rates during pregnancy were highest among women ages 20–24 (3.3%) and 25–29 (3.2%). Tobacco use during pregnancy was less common (less than 3%) among females younger than age 20 and women age 30 and older (Table 15).

## Medical and Health Services Utilization and Source of Payment for the Delivery (Tables 13–19)

### Use and timing of prenatal care

Among women who gave birth in 2023, 76.1% began prenatal care in the first trimester of pregnancy, down 1% from 77.0% in 2022 and the lowest percentage since comparable national data became available in 2016 (77.1%) (Table A, Table 16). Late (beginning in the third trimester) or no prenatal care increased 3% in 2023 to 7.0% from 6.8% in 2022 and higher than any year since comparable national data became available. A recent report describes changes in timing of prenatal care initiation and the number of prenatal care visits from 2019 through 2021 (20).

Table A Timing of prenatal care initiation: United States, 2016–2023

Year | First trimester | Late or no care^1^
2023 | 76.1 | 7.0
2022 | 77.0 | 6.8
2021 | 78.3 | 6.3
2020 | 77.7 | 6.2
2019 | 77.6 | 6.4
2018 | 77.5 | 6.2
2017 | 77.3 | 6.3
2016 | 77.1 | 6.2

1 Care starting in the third trimester or no care.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Prenatal care beginning in the first trimester decreased for the three largest race and Hispanic-origin groups: White (from 82.6% in 2022 to 82.4% in 2023), Hispanic (from 70.5% to 68.9%), and Black (from 67.6% to 66.3%) (Table 16) (15). Late or no prenatal care increased for Hispanic (9.1% to 9.7%) and Black (10.0% to 10.4%) women and was unchanged for White women (4.7%). Timing of prenatal care continued to vary by race and Hispanic origin in 2023. First trimester care ranged from 48.6% for Native Hawaiian and Other Pacific Islander women to 82.4% for White women; late or no prenatal care ranged from 4.7% for White women to 22.4% for Native Hawaiian and Other Pacific Islander women (Table 13).

Initiation of prenatal care in the first trimester was lower in 2023 than in 2022 for women in all age groups, decreasing from 59.1% to 57.6% for females younger than age 20, from 70.6% to 69.7% for ages 20–24, and from 77.1% to 76.4% for ages 25–29. For women in age groups 30 and older, first trimester care decreased from 80.9% to 80.1% for women ages 30–34, from 80.4% to 79.5% for ages 35–39, and from 76.8% to 75.8% for age 40 and older (Table 16) (15).

### Method of delivery

#### Cesarean delivery

In 2023, the cesarean delivery rate was 32.3%, up 1% from 2022 (32.1%) and 2% since the most recent low in 2019 (31.7%) (Table 17). The cesarean delivery rate peaked in 2009 at 32.9%, after increasing every year since 1996 (20.7%) (12).

The cesarean delivery rate increased 1% in 2023 for Hispanic (32.0%, up from 31.7% in 2022) and Black (37.0%, up from 36.8%) women and remained unchanged for White women (31.1%). Black women continued to have the highest cesarean delivery rate in 2023. Tables 13 and 14 show cesarean delivery rates for more detailed race and Hispanic-origin groups.

Changes from 2022 to 2023 in cesarean delivery rates varied by maternal age group (Table 18), increasing for age groups 25 and older (15). The largest increase was for women age 40 and older, increasing 1% from 47.7% in 2022 to 48.1% in 2023. Rates for groups younger than age 25 were unchanged. Cesarean delivery continued to be higher among older women compared with younger mothers; women age 40 and older were more than twice as likely to deliver by cesarean section (48.1%) than females younger than age 20 (18.9%).

Low-risk cesarean delivery—The low-risk cesarean delivery rate increased in 2023, to 26.6% from 26.3% in 2022 (Table 17). The low-risk cesarean delivery rate is cesarean delivery among nulliparous (first birth), term (37 completed weeks or more based on the obstetric estimate), singleton (one fetus), and cephalic (head-first) births. See Tables 13, 14, 17, and 18 for details by age and race and Hispanic origin of the mother.

Primary cesarean delivery—In 2023, the primary cesarean delivery rate, which measures cesarean deliveries among women who have not had a previous cesarean delivery, was 22.8%, up 1% from 22.5% in 2022 (Tables 17 and 18). A recent report describes trends in primary and repeat cesarean delivery through 2021 (21).

Vaginal birth after previous cesarean delivery—The rate of vaginal birth after previous cesarean delivery measures vaginal births among women with a previous cesarean delivery. In 2023, 15.1% of women with a previous cesarean delivered vaginally, up 3% from 14.6% in 2022 (Figure 3). The rate has increased every year since 2016, when comparable national data became available (see Tables 17 and 18 for details).

Figure 3 Vaginal birth after cesarean delivery: United States, 2016–2023

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 3 is a line graph of vaginal birth after cesarean delivery in the United States, 2016–2023.

### Source of payment for the delivery

The principal sources of payment for the delivery of most births in 2023 continued to be either private insurance or Medicaid; however, the percentage of births covered by private insurance declined from 2022 (from 51.2% to 51.0%), and the percentage of births covered by Medicaid increased (41.3% to 41.5%) (Table 19). The percentage of births in the category self-pay, generally considered to indicate uninsured deliveries, increased from 2022 (4.1% to 4.4%). The remainder of births were covered by other insurance (3.2% of births, down from 3.4% in 2022), which includes Indian Health Service, CHAMPUS or TRICARE, other government (federal, state, or local), or charity (15). Private insurance has been the most common principal source of payment since national data became available in 2016 (13). A recent report describes source of payment for the delivery by various maternal characteristics for 2021 (22).

Table 19 Principal source of payment for the delivery, by age and race and Hispanic origin of mother: United States, 2023

[Percentages are number of live births with specified source of payment per 100 live births in specified group]

Race and Hispanic origin of mother and source of payment | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54
All races and origins^1^ | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
Medicaid | 41.5 | 78.5 | 63.3 | 44.1 | 30.8 | 28.1 | 30.8
Private insurance | 51.0 | 14.4 | 28.3 | 47.9 | 62.2 | 64.9 | 61.3
Self-pay | 4.4 | 4.8 | 4.5 | 4.5 | 4.0 | 4.3 | 5.2
Other^2^ | 3.2 | 2.4 | 3.9 | 3.6 | 2.9 | 2.7 | 2.7
| Number
Total | 3,596,017 | 142,743 | 616,970 | 986,567 | 1,098,052 | 604,631 | 147,054
Not stated | 26,431 | 1,064 | 5,156 | 7,662 | 7,429 | 4,074 | 1,046
Non-Hispanic, single race^3^
Black: | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
Medicaid | 64.5 | 85.6 | 76.7 | 67.9 | 58.0 | 50.3 | 44.8
Private insurance | 30.4 | 11.0 | 18.8 | 26.8 | 36.5 | 43.9 | 49.2
Self-pay | 2.3 | 1.7 | 1.7 | 2.3 | 2.6 | 2.9 | 3.3
Other^2^ | 2.8 | 1.6 | 2.8 | 3.1 | 2.9 | 2.9 | 2.7
| Number
Total | 491,494 | 28,900 | 103,077 | 131,705 | 131,500 | 74,492 | 21,820
Not stated | 3,242 | 146 | 679 | 934 | 881 | 464 | 138
White: | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
Medicaid | 27.6 | 72.5 | 51.7 | 29.8 | 18.5 | 16.7 | 19.0
Private insurance | 65.1 | 22.5 | 39.8 | 62.2 | 74.9 | 76.8 | 73.3
Self-pay | 4.0 | 2.4 | 4.2 | 4.2 | 3.7 | 3.9 | 5.1
Other^2^ | 3.3 | 2.7 | 4.3 | 3.7 | 2.9 | 2.6 | 2.7
| Number
Total | 1,787,051 | 45,273 | 263,760 | 500,910 | 595,741 | 314,198 | 67,169
Not stated | 12,897 | 387 | 2,283 | 3,776 | 3,929 | 2,045 | 477
Hispanic^4^ | Percent
Total | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0 | 100.0
Medicaid | 58.8 | 79.6 | 71.3 | 59.2 | 49.8 | 47.8 | 50.3
Private insurance | 31.5 | 9.5 | 18.5 | 31.0 | 41.2 | 42.6 | 39.5
Self-pay | 6.7 | 8.5 | 6.7 | 6.5 | 6.2 | 7.1 | 7.7
Other^2^ | 3.0 | 2.3 | 3.5 | 3.3 | 2.7 | 2.6 | 2.6
| Number
Total | 945,200 | 58,714 | 207,702 | 270,317 | 240,489 | 131,623 | 36,355
Not stated | 6,432 | 455 | 1,604 | 1,900 | 1,444 | 803 | 226

1 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, and Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

2 Includes Indian Health Service, CHAMPUS or TRICARE, other government (federal, state, or local), or charity.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

By the three largest race and Hispanic-origin groups, the percentage of births covered by private insurance declined for Black (from 30.6% to 30.4%) and Hispanic (31.6% to 31.5%) women from 2022 to 2023 and did not change for White women (65.1%) (15). The percentage of births covered by Medicaid declined from 2022 to 2023 for White women (27.8% to 27.6%) but increased for Black (64.1% to 64.5%) and Hispanic (58.6% to 58.8%) women. See Tables 13 and 14 for information for additional race and Hispanic-origin groups.

By age of mother, Medicaid as the source of payment decreased for females younger than age 20 and women ages 25–29, increased for women ages 30–54, and was unchanged for women ages 20–24 (63.3%) from 2022 to 2023 (15). The largest increase was seen among women ages 35–39, from 27.4% to 28.1%. The percentages of births with Medicaid as the source of payment ranged from 28.1% for women ages 35–39 to 78.5% for those younger than age 20. Private insurance as the source of payment declined from 2022 to 2023 for females younger than age 20 and women ages 30–54, increased for women ages 25–29 (47.8% to 47.9%), and was essentially unchanged for women ages 20–24 (28.4% to 28.3%). Percentages with private insurance ranged from 14.4% for females younger than age 20 to 64.9% for women ages 35–39.

## Infant Health Characteristics (Tables 20–25)

Table 20 Births, by gestational age in weeks: United States, 2010–2023, and by race and Hispanic origin of mother: United States, 2016–2023

Race and Hispanic origin of mother and year | All births | Preterm^1^ | | | | | | Term^1^ | | | | Post term^1^ | Not stated
Race and Hispanic origin of mother and year | All births | Total under 37 | Total under 34 | Early | | | Late | Total 37–41 | Early | Full | Late | | Not stated
Race and Hispanic origin of mother and year | All births | Total under 37 | Total under 34 | Under 28 | 28–31 | 32–33 | 34–36 | Total 37–41 | 37–38 | 39–40 | 41 | 42 and over | Not stated
All races and origins^2^ | Number | Percent | | | | | | | | | | | Number
2023 | 3,596,017 | 10.41 | 2.76 | 0.64 | 0.92 | 1.20 | 7.64 | 89.34 | 29.84 | 54.94 | 4.56 | 0.26 | 2,642
2022 | 3,667,758 | 10.38 | 2.76 | 0.64 | 0.92 | 1.20 | 7.62 | 89.36 | 29.31 | 55.32 | 4.73 | 0.26 | 2,671
2021 | 3,664,292 | 10.49 | 2.81 | 0.64 | 0.95 | 1.22 | 7.67 | 89.27 | 28.76 | 55.90 | 4.61 | 0.25 | 2,992
2020 | 3,613,647 | 10.09 | 2.70 | 0.64 | 0.90 | 1.15 | 7.40 | 89.66 | 27.78 | 57.00 | 4.88 | 0.25 | 2,478
2019 | 3,747,540 | 10.23 | 2.77 | 0.66 | 0.93 | 1.18 | 7.46 | 89.52 | 27.31 | 57.02 | 5.19 | 0.25 | 2,406
2018 | 3,791,712 | 10.02 | 2.75 | 0.66 | 0.91 | 1.18 | 7.28 | 89.68 | 26.53 | 57.24 | 5.90 | 0.30 | 2,507
2017 | 3,855,500 | 9.93 | 2.76 | 0.67 | 0.92 | 1.17 | 7.17 | 89.74 | 26.00 | 57.49 | 6.25 | 0.33 | 2,759
2016 | 3,945,875 | 9.85 | 2.76 | 0.68 | 0.92 | 1.17 | 7.09 | 89.80 | 25.47 | 57.94 | 6.38 | 0.35 | 3,454
2015 | 3,978,497 | 9.63 | 2.76 | 0.68 | 0.91 | 1.17 | 6.87 | 89.98 | 24.99 | 58.47 | 6.51 | 0.40 | 2,926
2014 | 3,988,076 | 9.57 | 2.75 | 0.69 | 0.91 | 1.15 | 6.82 | 90.43 | 24.76 | 58.72 | 6.53 | 0.42 | 3,246
2013 | 3,932,181 | 9.62 | 2.79 | 0.70 | 0.92 | 1.17 | 6.83 | 90.38 | 24.81 | 58.85 | 6.31 | 0.41 | 7,467
2012 | 3,952,841 | 9.76 | 2.80 | 0.71 | 0.92 | 1.17 | 6.96 | 90.24 | 25.47 | 58.30 | 6.06 | 0.40 | 8,380
2011 | 3,953,590 | 9.81 | 2.81 | 0.70 | 0.93 | 1.18 | 6.99 | 90.19 | 26.09 | 57.51 | 6.16 | 0.43 | 9,290
2010 | 3,999,386 | 9.98 | 2.84 | 0.71 | 0.94 | 1.18 | 7.15 | 90.01 | 27.29 | 56.08 | 6.19 | 0.46 | 10,538
Non-Hispanic, single race^3^
Black:
2023 | 491,494 | 14.65 | 4.86 | 1.43 | 1.61 | 1.82 | 9.79 | 85.14 | 33.47 | 48.26 | 3.42 | 0.21 | 298
2022 | 511,439 | 14.59 | 4.89 | 1.47 | 1.56 | 1.86 | 9.70 | 85.18 | 32.73 | 48.81 | 3.65 | 0.23 | 326
2021 | 517,889 | 14.75 | 4.95 | 1.44 | 1.67 | 1.85 | 9.80 | 85.04 | 32.27 | 49.28 | 3.49 | 0.21 | 391
2020 | 529,811 | 14.36 | 4.82 | 1.47 | 1.58 | 1.77 | 9.54 | 85.43 | 31.22 | 50.47 | 3.74 | 0.21 | 300
2019 | 548,075 | 14.39 | 4.94 | 1.52 | 1.63 | 1.79 | 9.45 | 85.39 | 30.40 | 50.93 | 4.06 | 0.21 | 326
2018 | 552,029 | 14.13 | 4.90 | 1.51 | 1.60 | 1.79 | 9.23 | 85.62 | 29.64 | 51.34 | 4.64 | 0.25 | 384
2017 | 560,715 | 13.93 | 4.87 | 1.53 | 1.62 | 1.72 | 9.06 | 85.79 | 28.93 | 51.90 | 4.96 | 0.28 | 445
2016 | 558,622 | 13.77 | 4.93 | 1.56 | 1.61 | 1.75 | 8.84 | 85.94 | 28.48 | 52.42 | 5.04 | 0.30 | 506
White:
2023 | 1,787,051 | 9.44 | 2.28 | 0.44 | 0.76 | 1.09 | 7.16 | 90.22 | 28.30 | 56.72 | 5.20 | 0.34 | 911
2022 | 1,840,739 | 9.44 | 2.28 | 0.43 | 0.76 | 1.08 | 7.16 | 90.24 | 27.68 | 57.25 | 5.31 | 0.32 | 1,011
2021 | 1,887,656 | 9.50 | 2.31 | 0.44 | 0.77 | 1.10 | 7.18 | 90.19 | 27.04 | 57.93 | 5.23 | 0.31 | 1,215
2020 | 1,843,432 | 9.10 | 2.21 | 0.44 | 0.74 | 1.03 | 6.90 | 90.58 | 25.98 | 59.08 | 5.53 | 0.32 | 1,001
2019 | 1,915,912 | 9.26 | 2.27 | 0.44 | 0.77 | 1.06 | 6.99 | 90.42 | 25.56 | 59.01 | 5.84 | 0.32 | 924
2018 | 1,956,413 | 9.09 | 2.26 | 0.44 | 0.76 | 1.07 | 6.83 | 90.53 | 24.68 | 59.16 | 6.70 | 0.37 | 924
2017 | 1,992,461 | 9.05 | 2.30 | 0.46 | 0.77 | 1.06 | 6.76 | 90.54 | 24.16 | 59.27 | 7.11 | 0.40 | 1,051
2016 | 2,056,332 | 9.04 | 2.33 | 0.48 | 0.78 | 1.07 | 6.72 | 90.53 | 23.64 | 59.61 | 7.28 | 0.43 | 1,409
Hispanic^4^
2023 | 945,200 | 10.14 | 2.62 | 0.63 | 0.88 | 1.10 | 7.52 | 89.69 | 30.40 | 55.11 | 4.18 | 0.17 | 447
2022 | 937,421 | 10.06 | 2.60 | 0.60 | 0.88 | 1.12 | 7.46 | 89.77 | 30.10 | 55.24 | 4.42 | 0.17 | 421
2021 | 885,916 | 10.23 | 2.67 | 0.63 | 0.91 | 1.14 | 7.57 | 89.62 | 29.83 | 55.62 | 4.17 | 0.15 | 496
2020 | 866,713 | 9.84 | 2.52 | 0.60 | 0.84 | 1.07 | 7.32 | 90.01 | 29.00 | 56.61 | 4.41 | 0.15 | 348
2019 | 886,467 | 9.97 | 2.61 | 0.63 | 0.87 | 1.11 | 7.36 | 89.87 | 28.66 | 56.52 | 4.68 | 0.16 | 344
2018 | 886,210 | 9.73 | 2.56 | 0.62 | 0.84 | 1.09 | 7.17 | 90.07 | 28.05 | 56.83 | 5.19 | 0.20 | 382
2017 | 898,764 | 9.62 | 2.56 | 0.62 | 0.85 | 1.09 | 7.05 | 90.16 | 27.58 | 57.15 | 5.43 | 0.23 | 455
2016 | 918,447 | 9.45 | 2.98 | 0.62 | 0.84 | 1.08 | 6.92 | 90.30 | 27.02 | 57.85 | 5.43 | 0.25 | 676
All races and origins^2^ | Number
2023 | 3,596,017 | 373,902 | 99,255 | 23,096 | 33,153 | 43,006 | 274,647 | 3,210,174 | 1,072,092 | 1,974,300 | 163,782 | 9,299 | 2,642
2022 | 3,667,758 | 380,548 | 101,167 | 23,369 | 33,663 | 44,135 | 279,381 | 3,275,078 | 1,074,082 | 2,027,670 | 173,326 | 9,461 | 2,671
2021 | 3,664,292 | 383,979 | 103,004 | 23,527 | 34,731 | 44,746 | 280,975 | 3,268,342 | 1,052,935 | 2,046,786 | 168,621 | 8,979 | 2,992
2020 | 3,613,647 | 364,487 | 97,420 | 23,286 | 32,463 | 41,671 | 267,067 | 3,237,819 | 1,003,260 | 2,058,396 | 176,163 | 8,863 | 2,478
2019 | 3,747,540 | 383,061 | 103,759 | 24,758 | 34,748 | 44,253 | 279,302 | 3,352,638 | 1,022,874 | 2,135,518 | 194,246 | 9,435 | 2,406
2018 | 3,791,712 | 379,777 | 104,031 | 24,945 | 34,386 | 44,700 | 275,746 | 3,398,110 | 1,005,405 | 2,169,016 | 223,689 | 11,318 | 2,507
2017 | 3,855,500 | 382,726 | 106,417 | 25,913 | 35,476 | 45,028 | 276,309 | 3,457,455 | 1,001,601 | 2,214,983 | 240,871 | 12,560 | 2,759
2016 | 3,945,875 | 388,218 | 108,836 | 26,618 | 36,239 | 45,979 | 279,382 | 3,540,290 | 1,004,224 | 2,284,399 | 251,667 | 13,913 | 3,454
2015 | 3,978,497 | 382,786 | 109,660 | 26,996 | 36,149 | 46,515 | 273,126 | 3,577,072 | 993,599 | 2,324,474 | 258,999 | 15,713 | 2,926
2014 | 3,988,076 | 381,321 | 109,474 | 27,320 | 36,245 | 45,909 | 271,847 | 3,586,933 | 986,745 | 2,339,796 | 260,392 | 19,822 | 3,246
2013 | 3,932,181 | 377,655 | 109,435 | 27,550 | 36,096 | 45,789 | 268,220 | 3,283,457 | 973,569 | 2,309,888 | 247,476 | 16,126 | 7,467
2012 | 3,952,841 | 385,082 | 110,444 | 28,004 | 36,366 | 46,074 | 274,638 | 3,304,365 | 1,004,750 | 2,299,615 | 239,148 | 15,866 | 8,380
2011 | 3,953,590 | 386,855 | 111,002 | 27,737 | 36,758 | 46,507 | 275,853 | 3,297,649 | 1,029,157 | 2,268,492 | 242,999 | 16,797 | 9,290
2010 | 3,999,386 | 398,402 | 113,131 | 28,437 | 37,435 | 47,259 | 285,271 | 3,325,476 | 1,088,564 | 2,236,912 | 246,768 | 18,413 | 10,538
Non-Hispanic, single race^3^
Black:
2023 | 491,494 | 71,956 | 23,859 | 7,046 | 7,887 | 8,926 | 48,097 | 418,212 | 164,390 | 237,042 | 16,780 | 1,028 | 298
2022 | 511,439 | 74,553 | 24,986 | 7,496 | 7,984 | 9,506 | 49,567 | 435,385 | 167,263 | 249,451 | 18,671 | 1,175 | 326
2021 | 517,889 | 76,334 | 25,641 | 7,445 | 8,640 | 9,556 | 50,693 | 440,079 | 167,006 | 255,016 | 18,057 | 1,085 | 391
2020 | 529,811 | 76,059 | 25,537 | 7,802 | 8,381 | 9,354 | 50,522 | 452,357 | 165,321 | 267,237 | 19,799 | 1,095 | 300
2019 | 548,075 | 78,829 | 27,063 | 8,332 | 8,927 | 9,804 | 51,766 | 467,745 | 166,528 | 278,956 | 22,261 | 1,175 | 326
2018 | 552,029 | 77,939 | 27,008 | 8,348 | 8,804 | 9,856 | 50,931 | 472,316 | 163,530 | 283,202 | 25,584 | 1,390 | 384
2017 | 560,715 | 78,024 | 27,274 | 8,548 | 9,070 | 9,656 | 50,750 | 480,661 | 162,072 | 290,803 | 27,786 | 1,585 | 445
2016 | 558,622 | 76,834 | 27,501 | 8,729 | 8,987 | 9,785 | 49,333 | 479,630 | 158,937 | 292,539 | 28,154 | 1,652 | 506
White:
2023 | 1,787,051 | 168,654 | 40,736 | 7,789 | 13,523 | 19,424 | 127,918 | 1,611,436 | 505,444 | 1,013,077 | 92,915 | 6,050 | 911
2022 | 1,840,739 | 173,638 | 41,902 | 7,968 | 14,062 | 19,872 | 131,736 | 1,660,116 | 509,163 | 1,053,269 | 97,684 | 5,974 | 1,011
2021 | 1,887,656 | 179,123 | 43,671 | 8,223 | 14,603 | 20,845 | 135,452 | 1,701,379 | 510,021 | 1,092,775 | 98,583 | 5,939 | 1,215
2020 | 1,843,432 | 167,679 | 40,638 | 8,043 | 13,681 | 18,914 | 127,041 | 1,668,915 | 478,611 | 1,088,456 | 101,848 | 5,837 | 1,001
2019 | 1,915,912 | 177,339 | 43,532 | 8,487 | 14,735 | 20,310 | 133,807 | 1,731,535 | 489,542 | 1,130,124 | 111,869 | 6,114 | 924
2018 | 1,956,413 | 177,842 | 44,287 | 8,665 | 14,764 | 20,858 | 133,555 | 1,770,366 | 482,550 | 1,156,775 | 131,041 | 7,281 | 924
2017 | 1,992,461 | 180,322 | 45,761 | 9,200 | 15,429 | 21,132 | 134,561 | 1,803,063 | 481,048 | 1,180,394 | 141,621 | 8,025 | 1,051
2016 | 2,056,332 | 185,854 | 47,823 | 9,766 | 16,101 | 21,956 | 138,031 | 1,860,243 | 485,846 | 1,224,872 | 149,525 | 8,826 | 1,409
Hispanic^4^ | Number
2023 | 945,200 | 95,755 | 24,735 | 5,966 | 8,354 | 10,415 | 71,020 | 847,391 | 287,252 | 520,655 | 39,484 | 1,607 | 447
2022 | 937,421 | 94,306 | 24,408 | 5,653 | 8,289 | 10,466 | 69,898 | 841,129 | 282,083 | 517,597 | 41,449 | 1,565 | 421
2021 | 885,916 | 90,613 | 23,620 | 5,534 | 8,021 | 10,065 | 66,993 | 793,509 | 264,132 | 492,466 | 36,911 | 1,298 | 496
2020 | 866,713 | 85,224 | 21,790 | 5,241 | 7,273 | 9,276 | 63,434 | 779,828 | 251,210 | 490,413 | 38,205 | 1,313 | 348
2019 | 886,467 | 88,354 | 23,116 | 5,620 | 7,699 | 9,797 | 65,238 | 796,333 | 253,964 | 500,856 | 41,513 | 1,436 | 344
2018 | 886,210 | 86,186 | 22,637 | 5,490 | 7,467 | 9,680 | 63,549 | 797,905 | 248,463 | 503,429 | 46,013 | 1,737 | 382
2017 | 898,764 | 86,393 | 23,025 | 5,605 | 7,635 | 9,785 | 63,368 | 809,882 | 247,788 | 513,342 | 48,752 | 2,034 | 455
2016 | 918,447 | 86,691 | 23,195 | 5,649 | 7,665 | 9,881 | 63,496 | 828,783 | 247,999 | 530,951 | 49,833 | 2,297 | 676

1 Completed weeks based on the obstetric estimate of gestation; see Technical Notes in this report.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statsitics, National Vital Statistics System, natality data file.

Table 21 Births, by gestational age in weeks, and age and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin and age of mother | All births | Preterm^1^ | | | | | Term^1^ | | | | Post term^1^ | Not stated
Race and Hispanic origin and age of mother | All births | Total under 37 | Early | | | Late | Total 37–41 | Early | Full | Late | | Not stated
Race and Hispanic origin and age of mother | All births | Total under 37 | Under 28 | 28–31 | 32–33 | 34–36 | Total 37–41 | 37–38 | 39–40 | 41 | 42 and over | Not stated
All races and origins^2^ | Number | Percent | | | | | | | | | | Number
All ages | 3,596,017 | 10.41 | 0.64 | 0.92 | 1.20 | 7.64 | 89.34 | 29.84 | 54.94 | 4.56 | 0.26 | 2,642
Younger than 15 | 1,766 | 17.80 | 1.65 | 2.28 | 1.88 | 12.00 | 82.08 | 28.50 | 49.49 | 4.10 | * | 8
15–19 | 140,977 | 11.00 | 0.94 | 1.03 | 1.28 | 7.74 | 88.83 | 29.89 | 54.36 | 4.58 | 0.17 | 150
20–24 | 616,970 | 9.78 | 0.69 | 0.86 | 1.09 | 7.14 | 89.98 | 29.54 | 55.74 | 4.69 | 0.24 | 532
25–29 | 986,567 | 9.64 | 0.60 | 0.84 | 1.09 | 7.11 | 90.10 | 29.27 | 55.96 | 4.88 | 0.26 | 687
30–34 | 1,098,052 | 10.08 | 0.59 | 0.89 | 1.16 | 7.44 | 89.65 | 29.15 | 55.57 | 4.93 | 0.27 | 715
35–39 | 604,631 | 11.65 | 0.65 | 1.02 | 1.37 | 8.60 | 88.07 | 31.13 | 53.07 | 3.87 | 0.28 | 430
40–44 | 136,333 | 14.36 | 0.78 | 1.39 | 1.70 | 10.48 | 85.40 | 34.31 | 49.13 | 1.95 | 0.24 | 102
45–54 | 10,721 | 20.64 | 1.22 | 2.12 | 3.30 | 14.00 | 79.02 | 38.21 | 39.37 | 1.44 | 0.34 | 18
Non-Hispanic, single race^3^
Black:
All ages | 491,494 | 14.65 | 1.43 | 1.61 | 1.82 | 9.79 | 85.14 | 33.47 | 48.26 | 3.42 | 0.21 | 298
Younger than 15 | 486 | 16.94 | 2.07 | * | 2.27 | 11.16 | 83.06 | 30.79 | 47.31 | 4.96 | * | 2
15–19 | 28,414 | 13.30 | 1.54 | 1.45 | 1.63 | 8.68 | 86.56 | 32.58 | 50.47 | 3.51 | 0.14 | 27
20–24 | 103,077 | 12.93 | 1.36 | 1.42 | 1.52 | 8.63 | 86.89 | 32.79 | 50.63 | 3.48 | 0.18 | 74
25–29 | 131,705 | 13.65 | 1.34 | 1.51 | 1.71 | 9.09 | 86.14 | 32.56 | 49.94 | 3.64 | 0.22 | 70
30–34 | 131,500 | 15.09 | 1.44 | 1.64 | 1.87 | 10.14 | 84.67 | 33.20 | 47.76 | 3.71 | 0.24 | 69
35–39 | 74,492 | 16.92 | 1.59 | 1.79 | 2.15 | 11.40 | 82.85 | 35.29 | 44.59 | 2.97 | 0.23 | 44
40–44 | 19,925 | 19.28 | 1.62 | 2.34 | 2.41 | 12.92 | 80.59 | 38.63 | 40.55 | 1.40 | 0.14 | 11
45–54 | 1,895 | 29.20 | 2.16 | 3.59 | 5.60 | 17.85 | 70.49 | 39.92 | 29.14 | 1.43 | * | 1
White:
All ages | 1,787,051 | 9.44 | 0.44 | 0.76 | 1.09 | 7.16 | 90.22 | 28.30 | 56.72 | 5.20 | 0.34 | 911
Younger than 15 | 351 | 18.29 | * | 3.14 | * | 12.00 | 81.71 | 24.86 | 53.71 | 3.14 | * | 1
15–19 | 44,922 | 10.73 | 0.79 | 0.98 | 1.32 | 7.64 | 89.12 | 29.35 | 55.45 | 4.32 | 0.15 | 37
20–24 | 263,760 | 9.34 | 0.51 | 0.74 | 1.06 | 7.02 | 90.35 | 28.78 | 56.62 | 4.94 | 0.32 | 183
25–29 | 500,910 | 8.93 | 0.42 | 0.72 | 1.01 | 6.78 | 90.75 | 28.04 | 57.26 | 5.44 | 0.33 | 210
30–34 | 595,741 | 9.01 | 0.38 | 0.72 | 1.04 | 6.87 | 90.64 | 27.41 | 57.53 | 5.71 | 0.34 | 259
35–39 | 314,198 | 10.27 | 0.43 | 0.81 | 1.20 | 7.84 | 89.34 | 28.99 | 55.59 | 4.76 | 0.38 | 183
40–44 | 62,607 | 12.41 | 0.52 | 1.00 | 1.50 | 9.39 | 87.20 | 31.83 | 52.66 | 2.71 | 0.39 | 36
45–54 | 4,562 | 16.91 | 0.90 | 1.75 | 2.24 | 12.02 | 82.61 | 37.72 | 42.85 | 2.04 | 0.48 | 2
Race and Hispanic origin and age of mother | All births | Preterm^1^ | | | | | Term^1^ | | | | Post term^1^ | Not stated
Race and Hispanic origin and age of mother | All births | Total under 37 | Early | | | Late | Total 37–41 | Early | Full | Late | | Not stated
Race and Hispanic origin and age of mother | All births | Total under 37 | Under 28 | 28–31 | 32–33 | 34–36 | Total 37–41 | 37–38 | 39–40 | 41 | 42 and over | Not stated
Hispanic^4^ | Number | Percent | | | | | | | | | | Number
All ages | 945,200 | 10.14 | 0.63 | 0.88 | 1.10 | 7.52 | 89.69 | 30.40 | 55.11 | 4.18 | 0.17 | 447
Younger than 15 | 800 | 17.59 | 1.63 | 2.14 | 1.51 | 12.31 | 82.16 | 28.39 | 49.75 | 4.02 | * | 4
15–19 | 57,914 | 9.99 | 0.76 | 0.86 | 1.02 | 7.35 | 89.80 | 28.97 | 55.54 | 5.29 | 0.21 | 59
20–24 | 207,702 | 8.72 | 0.59 | 0.73 | 0.90 | 6.50 | 91.10 | 28.80 | 57.35 | 4.95 | 0.18 | 103
25–29 | 270,317 | 9.10 | 0.57 | 0.75 | 0.97 | 6.81 | 90.72 | 29.67 | 56.56 | 4.49 | 0.17 | 114
30–34 | 240,489 | 10.41 | 0.64 | 0.96 | 1.14 | 7.68 | 89.42 | 30.60 | 54.76 | 4.06 | 0.17 | 111
35–39 | 131,623 | 12.48 | 0.70 | 1.11 | 1.46 | 9.21 | 87.38 | 33.14 | 51.37 | 2.87 | 0.14 | 41
40–44 | 34,043 | 15.29 | 0.81 | 1.46 | 1.66 | 11.37 | 84.59 | 35.89 | 47.44 | 1.27 | 0.11 | 12
45–54 | 2,312 | 21.26 | 1.47 | 2.12 | 3.46 | 14.21 | 78.61 | 39.63 | 38.28 | 0.69 | * | 3

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Completed weeks based on the obstetric estimate of gestation; see Technical Notes in this report.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Heatlh Statistics, National Vital Statistics System, natality data file.

Table 22 Births, by birthweight: United States, 2010–2023, and by age and race and Hispanic origin of mother: United States, 2016–2023

Race and Hispanic origin of mother and year | All births | Birthweight (grams)^1^
Race and Hispanic origin of mother and year | All births | Low birthweight | | | | | | | 2,500–2,999 | 3,000–3,499 | 3,500–3,999 | 4,000–4,499 | 4,500–4,999 | 5,000 or more | Not stated
Race and Hispanic origin of mother and year | All births | Total under 2,500 | Very low birthweight | | | | 1,500–1,999 | 2,000–2,499 | 2,500–2,999 | 3,000–3,499 | 3,500–3,999 | 4,000–4,499 | 4,500–4,999 | 5,000 or more | Not stated
Race and Hispanic origin of mother and year | All births | Total under 2,500 | Total under 1,500 | Less than 500 | 500–999 | 1,000–1,499 | 1,500–1,999 | 2,000–2,499 | 2,500–2,999 | 3,000–3,499 | 3,500–3,999 | 4,000–4,499 | 4,500–4,999 | 5,000 or more | Not stated
All races and origins^2^ | Number | Percent | | | | | | | | | | | | | Number
2023 | 3,596,017 | 8.58 | 1.36 | 0.13 | 0.50 | 0.73 | 1.66 | 5.56 | 19.72 | 39.09 | 25.51 | 6.20 | 0.80 | 0.09 | 2,915
2022 | 3,667,758 | 8.60 | 1.36 | 0.13 | 0.49 | 0.73 | 1.67 | 5.57 | 19.68 | 39.00 | 25.58 | 6.23 | 0.82 | 0.09 | 2,990
2021 | 3,664,292 | 8.52 | 1.38 | 0.13 | 0.51 | 0.75 | 1.68 | 5.46 | 19.25 | 38.85 | 25.93 | 6.47 | 0.87 | 0.10 | 3,331
2020 | 3,613,647 | 8.24 | 1.34 | 0.13 | 0.49 | 0.71 | 1.61 | 5.29 | 19.15 | 38.94 | 26.18 | 6.51 | 0.87 | 0.10 | 2,977
2019 | 3,747,540 | 8.31 | 1.38 | 0.14 | 0.50 | 0.74 | 1.63 | 5.30 | 19.07 | 39.07 | 26.09 | 6.49 | 0.87 | 0.10 | 3,668
2018 | 3,791,712 | 8.28 | 1.38 | 0.14 | 0.50 | 0.74 | 1.62 | 5.28 | 18.75 | 38.76 | 26.44 | 6.72 | 0.94 | 0.11 | 2,932
2017 | 3,855,500 | 8.28 | 1.41 | 0.14 | 0.52 | 0.74 | 1.63 | 5.25 | 18.72 | 38.76 | 26.44 | 6.75 | 0.95 | 0.11 | 3,002
2016 | 3,945,875 | 8.17 | 1.40 | 0.14 | 0.52 | 0.74 | 1.59 | 5.17 | 18.54 | 38.76 | 26.60 | 6.85 | 0.97 | 0.11 | 4,518
2015 | 3,978,497 | 8.07 | 1.40 | 0.15 | 0.52 | 0.73 | 1.58 | 5.09 | 18.36 | 38.84 | 26.73 | 6.90 | 0.98 | 0.12 | 3,621
2014 | 3,988,076 | 8.00 | 1.40 | 0.15 | 0.52 | 0.74 | 1.56 | 5.04 | 18.27 | 38.80 | 26.88 | 6.94 | 0.99 | 0.12 | 3,270
2013 | 3,932,181 | 8.02 | 1.41 | 0.15 | 0.53 | 0.73 | 1.56 | 5.05 | 18.22 | 38.93 | 26.85 | 6.86 | 0.99 | 0.11 | 4,452
2012 | 3,952,841 | 7.99 | 1.42 | 0.15 | 0.54 | 0.73 | 1.56 | 5.01 | 18.28 | 39.00 | 26.81 | 6.83 | 0.97 | 0.12 | 4,008
2011 | 3,953,590 | 8.10 | 1.44 | 0.15 | 0.54 | 0.75 | 1.58 | 5.08 | 18.44 | 39.13 | 26.56 | 6.71 | 0.95 | 0.11 | 4,570
2010 | 3,999,386 | 8.15 | 1.45 | 0.15 | 0.55 | 0.75 | 1.59 | 5.11 | 18.63 | 39.21 | 26.41 | 6.58 | 0.92 | 0.11 | 3,964
Non-Hispanic, single race^3^
Black:
2023 | 491,494 | 14.80 | 2.86 | 0.34 | 1.12 | 1.40 | 2.87 | 9.07 | 26.48 | 37.27 | 17.51 | 3.45 | 0.44 | 0.06 | 491
2022 | 511,439 | 14.75 | 2.89 | 0.34 | 1.15 | 1.40 | 2.85 | 9.01 | 26.40 | 37.23 | 17.57 | 3.52 | 0.47 | 0.06 | 528
2021 | 517,889 | 14.66 | 2.91 | 0.32 | 1.15 | 1.44 | 2.91 | 8.84 | 26.08 | 37.38 | 17.74 | 3.58 | 0.49 | 0.06 | 580
2020 | 529,811 | 14.19 | 2.86 | 0.34 | 1.13 | 1.39 | 2.79 | 8.53 | 25.90 | 37.60 | 18.14 | 3.61 | 0.49 | 0.07 | 569
2019 | 548,075 | 14.15 | 2.94 | 0.36 | 1.15 | 1.43 | 2.79 | 8.43 | 25.75 | 37.96 | 18.01 | 3.59 | 0.47 | 0.06 | 688
2018 | 552,029 | 14.07 | 2.92 | 0.35 | 1.16 | 1.41 | 2.79 | 8.35 | 25.44 | 37.90 | 18.33 | 3.68 | 0.51 | 0.07 | 571
2017 | 560,715 | 13.89 | 2.95 | 0.36 | 1.18 | 1.41 | 2.72 | 8.22 | 25.44 | 37.96 | 18.37 | 3.76 | 0.51 | 0.07 | 642
2016 | 558,622 | 13.68 | 2.95 | 0.37 | 1.20 | 1.38 | 2.67 | 8.06 | 25.38 | 38.24 | 18.42 | 3.69 | 0.52 | 0.07 | 936
White:
2023 | 1,787,051 | 7.04 | 1.00 | 0.08 | 0.34 | 0.58 | 1.38 | 4.66 | 16.85 | 38.43 | 28.91 | 7.67 | 1.01 | 0.10 | 1,069
2022 | 1,840,739 | 7.12 | 1.01 | 0.08 | 0.34 | 0.59 | 1.41 | 4.70 | 16.84 | 38.38 | 28.91 | 7.65 | 0.99 | 0.10 | 1,125
2021 | 1,887,656 | 7.03 | 1.02 | 0.08 | 0.35 | 0.59 | 1.41 | 4.60 | 16.52 | 38.18 | 29.21 | 7.89 | 1.07 | 0.11 | 1,313
2020 | 1,843,432 | 6.84 | 0.99 | 0.08 | 0.34 | 0.56 | 1.35 | 4.50 | 16.37 | 38.18 | 29.46 | 7.96 | 1.07 | 0.12 | 1,144
2019 | 1,915,912 | 6.89 | 1.02 | 0.08 | 0.35 | 0.59 | 1.39 | 4.49 | 16.35 | 38.24 | 29.37 | 7.96 | 1.08 | 0.11 | 1,550
2018 | 1,956,413 | 6.91 | 1.02 | 0.09 | 0.34 | 0.58 | 1.38 | 4.52 | 16.01 | 37.80 | 29.74 | 8.25 | 1.16 | 0.12 | 1,259
2017 | 1,992,461 | 7.00 | 1.05 | 0.09 | 0.36 | 0.60 | 1.40 | 4.54 | 16.05 | 37.68 | 29.70 | 8.28 | 1.17 | 0.12 | 1,211
2016 | 2,056,332 | 6.97 | 1.07 | 0.09 | 0.37 | 0.61 | 1.39 | 4.51 | 15.88 | 37.59 | 29.82 | 8.39 | 1.21 | 0.12 | 2,212
Hispanic^4^ | Number | Percent | | | | | | | | | | | | | Number
2023 | 945,200 | 7.92 | 1.26 | 0.13 | 0.47 | 0.66 | 1.52 | 5.14 | 20.19 | 40.84 | 24.79 | 5.47 | 0.70 | 0.09 | 493
2022 | 937,421 | 7.87 | 1.24 | 0.12 | 0.45 | 0.67 | 1.51 | 5.12 | 20.15 | 40.66 | 24.93 | 5.54 | 0.75 | 0.10 | 479
2021 | 885,916 | 7.82 | 1.28 | 0.12 | 0.47 | 0.69 | 1.52 | 5.02 | 19.55 | 40.58 | 25.35 | 5.82 | 0.78 | 0.10 | 594
2020 | 866,713 | 7.40 | 1.19 | 0.12 | 0.45 | 0.63 | 1.43 | 4.77 | 19.41 | 40.63 | 25.74 | 5.92 | 0.79 | 0.11 | 436
2019 | 886,467 | 7.55 | 1.27 | 0.12 | 0.47 | 0.68 | 1.45 | 4.83 | 19.23 | 40.83 | 25.62 | 5.89 | 0.78 | 0.10 | 575
2018 | 886,210 | 7.49 | 1.24 | 0.12 | 0.46 | 0.66 | 1.43 | 4.81 | 19.01 | 40.64 | 25.90 | 6.02 | 0.83 | 0.11 | 381
2017 | 898,764 | 7.43 | 1.26 | 0.13 | 0.47 | 0.66 | 1.42 | 4.76 | 18.86 | 40.76 | 25.95 | 6.02 | 0.85 | 0.11 | 428
2016 | 918,447 | 7.32 | 1.24 | 0.13 | 0.46 | 0.65 | 1.41 | 4.68 | 18.76 | 40.79 | 26.06 | 6.10 | 0.85 | 0.12 | 556
All races and origins^2^ | Number
2023 | 3,596,017 | 308,263 | 48,832 | 4,780 | 17,826 | 26,226 | 59,591 | 199,840 | 708,655 | 1,404,466 | 916,755 | 222,852 | 28,842 | 3,269 | 2,915
2022 | 3,667,758 | 315,288 | 49,871 | 4,879 | 18,087 | 26,905 | 61,182 | 204,235 | 721,299 | 1,429,131 | 937,571 | 228,179 | 29,923 | 3,377 | 2,990
2021 | 3,664,292 | 311,932 | 50,551 | 4,629 | 18,512 | 27,410 | 61,585 | 199,796 | 704,766 | 1,422,368 | 949,323 | 236,987 | 31,964 | 3,621 | 3,331
2020 | 3,613,647 | 297,604 | 48,326 | 4,790 | 17,805 | 25,731 | 58,162 | 191,116 | 691,557 | 1,405,907 | 945,295 | 235,023 | 31,500 | 3,784 | 2,977
2019 | 3,747,540 | 311,245 | 51,733 | 5,189 | 18,839 | 27,705 | 61,205 | 198,307 | 713,859 | 1,462,658 | 976,609 | 243,153 | 32,694 | 3,654 | 3,668
2018 | 3,791,712 | 313,752 | 52,171 | 5,303 | 18,970 | 27,898 | 61,509 | 200,072 | 710,444 | 1,468,639 | 1,001,803 | 254,704 | 35,435 | 4,003 | 2,932
2017 | 3,855,500 | 318,873 | 54,135 | 5,470 | 19,979 | 28,686 | 62,605 | 202,133 | 721,165 | 1,493,081 | 1,018,613 | 260,042 | 36,493 | 4,231 | 3,002
2016 | 3,945,875 | 321,839 | 55,110 | 5,710 | 20,323 | 29,077 | 62,863 | 203,866 | 730,710 | 1,527,707 | 1,048,476 | 269,865 | 38,264 | 4,496 | 4,518
2015 | 3,978,497 | 320,869 | 55,592 | 5,863 | 20,689 | 29,040 | 62,862 | 202,415 | 729,673 | 1,544,024 | 1,062,456 | 274,404 | 38,796 | 4,654 | 3,621
2014 | 3,988,076 | 318,847 | 55,947 | 5,936 | 20,721 | 29,290 | 61,992 | 200,908 | 727,987 | 1,546,274 | 1,071,007 | 276,592 | 39,353 | 4,746 | 3,270
2013 | 3,932,181 | 315,099 | 55,458 | 5,945 | 20,866 | 28,647 | 61,238 | 198,403 | 715,764 | 1,529,258 | 1,054,767 | 269,594 | 38,834 | 4,413 | 4,452
2012 | 3,952,841 | 315,709 | 56,252 | 5,947 | 21,432 | 28,873 | 61,499 | 197,958 | 721,840 | 1,540,161 | 1,058,604 | 269,581 | 38,288 | 4,650 | 4,008
2011 | 3,953,590 | 319,711 | 56,754 | 5,942 | 21,289 | 29,523 | 62,504 | 200,453 | 728,201 | 1,545,355 | 1,048,902 | 265,040 | 37,475 | 4,336 | 4,570
2010 | 3,999,386 | 325,563 | 57,841 | 5,980 | 22,015 | 29,846 | 63,427 | 204,295 | 744,181 | 1,566,755 | 1,055,004 | 262,997 | 36,706 | 4,216 | 3,964
Non-Hispanic, single race^3^
Black:
2023 | 491,494 | 72,673 | 14,048 | 1,654 | 5,500 | 6,894 | 14,072 | 44,553 | 130,032 | 182,975 | 85,981 | 16,919 | 2,138 | 285 | 491
2022 | 511,439 | 75,359 | 14,774 | 1,723 | 5,892 | 7,159 | 14,557 | 46,028 | 134,893 | 190,192 | 89,775 | 17,984 | 2,387 | 321 | 528
2021 | 517,889 | 75,837 | 15,036 | 1,639 | 5,958 | 7,439 | 15,068 | 45,733 | 134,892 | 193,393 | 91,772 | 18,543 | 2,540 | 332 | 580
2020 | 529,811 | 75,085 | 15,146 | 1,806 | 5,985 | 7,355 | 14,785 | 45,154 | 137,053 | 198,979 | 96,025 | 19,101 | 2,618 | 381 | 569
2019 | 548,075 | 77,475 | 16,089 | 1,954 | 6,315 | 7,820 | 15,261 | 46,125 | 140,963 | 207,795 | 98,585 | 19,641 | 2,593 | 335 | 688
2018 | 552,029 | 77,584 | 16,127 | 1,941 | 6,406 | 7,780 | 15,411 | 46,046 | 140,295 | 209,028 | 101,089 | 20,285 | 2,806 | 371 | 571
2017 | 560,715 | 77,815 | 16,544 | 2,024 | 6,597 | 7,923 | 15,228 | 46,043 | 142,459 | 212,599 | 102,878 | 21,065 | 2,854 | 403 | 642
2016 | 558,622 | 76,299 | 16,465 | 2,083 | 6,675 | 7,707 | 14,885 | 44,949 | 141,557 | 213,260 | 102,702 | 20,571 | 2,880 | 417 | 936
Non-Hispanic, single race^3^ | Number
White:
2023 | 1,787,051 | 125,668 | 17,914 | 1,436 | 6,072 | 10,406 | 24,610 | 83,144 | 300,962 | 686,320 | 516,300 | 136,914 | 17,980 | 1,838 | 1,069
2022 | 1,840,739 | 130,976 | 18,565 | 1,521 | 6,266 | 10,778 | 25,879 | 86,532 | 309,819 | 706,130 | 531,886 | 140,719 | 18,242 | 1,842 | 1,125
2021 | 1,887,656 | 132,551 | 19,157 | 1,471 | 6,589 | 11,097 | 26,587 | 86,807 | 311,569 | 720,236 | 550,917 | 148,810 | 20,181 | 2,079 | 1,313
2020 | 1,843,432 | 126,034 | 18,182 | 1,521 | 6,263 | 10,398 | 24,881 | 82,971 | 301,674 | 703,331 | 542,775 | 146,626 | 19,719 | 2,129 | 1,144
2019 | 1,915,912 | 131,959 | 19,443 | 1,587 | 6,643 | 11,213 | 26,572 | 85,944 | 312,909 | 732,022 | 562,273 | 152,340 | 20,720 | 2,139 | 1,550
2018 | 1,956,413 | 135,185 | 19,872 | 1,721 | 6,719 | 11,432 | 26,964 | 88,349 | 313,105 | 739,031 | 581,499 | 161,395 | 22,645 | 2,294 | 1,259
2017 | 1,992,461 | 139,358 | 20,981 | 1,752 | 7,233 | 11,996 | 27,968 | 90,409 | 319,523 | 750,331 | 591,376 | 164,898 | 23,299 | 2,465 | 1,211
2016 | 2,056,332 | 143,254 | 21,979 | 1,888 | 7,565 | 12,526 | 28,578 | 92,697 | 326,279 | 772,165 | 612,641 | 172,434 | 24,781 | 2,566 | 2,212
Hispanic^4^
2023 | 945,200 | 74,860 | 11,932 | 1,216 | 4,486 | 6,230 | 14,335 | 48,593 | 190,745 | 385,797 | 234,159 | 51,672 | 6,633 | 841 | 493
2022 | 937,421 | 73,767 | 11,622 | 1,121 | 4,262 | 6,239 | 14,180 | 47,965 | 188,801 | 380,957 | 233,558 | 51,942 | 7,016 | 901 | 479
2021 | 885,916 | 69,238 | 11,336 | 1,024 | 4,179 | 6,133 | 13,471 | 44,431 | 173,097 | 359,282 | 224,461 | 51,483 | 6,866 | 895 | 594
2020 | 866,713 | 64,092 | 10,344 | 998 | 3,890 | 5,456 | 12,394 | 41,354 | 168,111 | 351,994 | 223,005 | 51,290 | 6,857 | 928 | 436
2019 | 886,467 | 66,912 | 11,223 | 1,105 | 4,135 | 5,983 | 12,869 | 42,820 | 170,366 | 361,725 | 226,969 | 52,185 | 6,880 | 855 | 575
2018 | 886,210 | 66,310 | 11,006 | 1,084 | 4,040 | 5,882 | 12,706 | 42,598 | 168,418 | 359,966 | 229,450 | 53,359 | 7,358 | 968 | 381
2017 | 898,764 | 66,766 | 11,275 | 1,137 | 4,229 | 5,909 | 12,772 | 42,719 | 169,467 | 366,198 | 233,157 | 54,096 | 7,631 | 1,021 | 428
2016 | 918,447 | 67,210 | 11,378 | 1,175 | 4,237 | 5,966 | 12,910 | 42,922 | 172,171 | 374,434 | 239,210 | 55,983 | 7,770 | 1,113 | 556

1 Equivalents of gram weights in pounds and ounces are shown in the User Guide; see reference 9 in this report.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 23 Births, by birthweight and age and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin and age of mother | All births | Birthweight (grams)^1^
Race and Hispanic origin and age of mother | All births | Low birthweight | | | | | | | 2,500–2,999 | 3,000–3,499 | 3,500–3,999 | 4,000–4,499 | 4,500–4,999 | 5,000 or more | Not stated
Race and Hispanic origin and age of mother | All births | | Very low birthweight | | | | 1,500–1,999 | 2,000–2,499 | 2,500–2,999 | 3,000–3,499 | 3,500–3,999 | 4,000–4,499 | 4,500–4,999 | 5,000 or more | Not stated
Race and Hispanic origin and age of mother | All births | Total under 2,500 | Total under 1,500 | Less than 500 | 500–999 | 1,000–1,499 | 1,500–1,999 | 2,000–2,499 | 2,500–2,999 | 3,000–3,499 | 3,500–3,999 | 4,000–4,499 | 4,500–4,999 | 5,000 or more | Not stated
All races and origins^2^ | Number | Percent | | | | | | | | | | | | | Number
All ages | 3,596,017 | 8.58 | 1.36 | 0.13 | 0.50 | 0.73 | 1.66 | 5.56 | 19.72 | 39.09 | 25.51 | 6.20 | 0.80 | 0.09 | 2,915
Younger than 15 | 1,766 | 15.77 | 3.06 | * | 0.74 | 1.93 | 2.61 | 10.10 | 28.42 | 39.53 | 14.86 | 1.30 | * | * | 3
15–19 | 140,977 | 11.11 | 1.77 | 0.21 | 0.68 | 0.88 | 1.96 | 7.37 | 25.96 | 40.85 | 18.66 | 3.10 | 0.28 | 0.03 | 108
20–24 | 616,970 | 8.93 | 1.38 | 0.15 | 0.52 | 0.71 | 1.59 | 5.96 | 21.93 | 40.74 | 23.04 | 4.78 | 0.52 | 0.05 | 540
25–29 | 986,567 | 7.95 | 1.25 | 0.13 | 0.46 | 0.66 | 1.53 | 5.18 | 19.11 | 39.43 | 26.31 | 6.31 | 0.79 | 0.09 | 765
30–34 | 1,098,052 | 7.98 | 1.27 | 0.12 | 0.45 | 0.69 | 1.57 | 5.14 | 18.46 | 38.57 | 27.01 | 6.96 | 0.92 | 0.10 | 887
35–39 | 604,631 | 9.04 | 1.44 | 0.12 | 0.52 | 0.80 | 1.83 | 5.78 | 19.00 | 37.82 | 26.15 | 6.87 | 0.99 | 0.12 | 486
40–44 | 136,333 | 10.93 | 1.88 | 0.13 | 0.66 | 1.08 | 2.32 | 6.74 | 20.77 | 37.37 | 23.73 | 6.12 | 0.93 | 0.14 | 107
45–54 | 10,721 | 16.60 | 2.91 | 0.24 | 1.16 | 1.50 | 4.07 | 9.62 | 23.01 | 34.58 | 20.46 | 4.65 | 0.63 | * | 19
Non-Hispanic, single race^3^
Black:
All ages | 491,494 | 14.80 | 2.86 | 0.34 | 1.12 | 1.40 | 2.87 | 9.07 | 26.48 | 37.27 | 17.51 | 3.45 | 0.44 | 0.06 | 491
Younger than 15 | 486 | 20.37 | 3.09 | * | * | * | 3.70 | 13.58 | 30.04 | 40.53 | 8.85 | * | * | * | -
15–19 | 28,414 | 16.68 | 2.93 | 0.41 | 1.13 | 1.39 | 2.78 | 10.98 | 32.45 | 37.02 | 12.09 | 1.60 | 0.15 | * | 23
20–24 | 103,077 | 14.96 | 2.65 | 0.33 | 1.07 | 1.26 | 2.62 | 9.70 | 29.21 | 38.42 | 14.90 | 2.26 | 0.22 | 0.03 | 106
25–29 | 131,705 | 14.06 | 2.65 | 0.31 | 1.04 | 1.29 | 2.74 | 8.68 | 26.29 | 38.09 | 17.72 | 3.37 | 0.40 | 0.05 | 141
30–34 | 131,500 | 14.24 | 2.85 | 0.34 | 1.10 | 1.41 | 2.89 | 8.50 | 24.88 | 36.85 | 19.33 | 4.09 | 0.55 | 0.06 | 132
35–39 | 74,492 | 15.25 | 3.24 | 0.36 | 1.25 | 1.64 | 3.14 | 8.87 | 23.99 | 35.83 | 19.60 | 4.57 | 0.64 | 0.11 | 67
40–44 | 19,925 | 17.03 | 3.64 | 0.31 | 1.45 | 1.87 | 3.60 | 9.79 | 25.05 | 34.89 | 17.96 | 4.36 | 0.64 | 0.07 | 16
45–54 | 1,895 | 25.15 | 5.77 | * | 2.44 | 2.86 | 6.30 | 13.08 | 25.62 | 29.96 | 15.56 | 3.23 | * | * | 6
White:
All ages | 1,787,051 | 7.04 | 1.00 | 0.08 | 0.34 | 0.58 | 1.38 | 4.66 | 16.85 | 38.43 | 28.91 | 7.67 | 1.01 | 0.10 | 1,069
Younger than 15 | 351 | 13.11 | 3.70 | * | * | 2.85 | * | 7.69 | 24.50 | 36.47 | 23.93 | * | * | * | -
15–19 | 44,922 | 10.00 | 1.53 | 0.15 | 0.57 | 0.80 | 1.84 | 6.63 | 21.90 | 40.92 | 22.61 | 4.15 | 0.39 | 0.03 | 24
20–24 | 263,760 | 7.49 | 1.08 | 0.10 | 0.39 | 0.59 | 1.37 | 5.05 | 19.13 | 40.29 | 26.30 | 6.05 | 0.68 | 0.06 | 165
25–29 | 500,910 | 6.63 | 0.96 | 0.08 | 0.33 | 0.55 | 1.30 | 4.37 | 16.46 | 38.67 | 29.49 | 7.67 | 0.97 | 0.10 | 254
30–34 | 595,741 | 6.51 | 0.92 | 0.07 | 0.30 | 0.55 | 1.30 | 4.29 | 15.81 | 37.95 | 30.16 | 8.35 | 1.11 | 0.10 | 381
35–39 | 314,198 | 7.42 | 1.01 | 0.07 | 0.34 | 0.60 | 1.49 | 4.91 | 16.49 | 37.30 | 29.20 | 8.28 | 1.19 | 0.13 | 195
40–44 | 62,607 | 8.97 | 1.30 | 0.08 | 0.42 | 0.80 | 1.82 | 5.85 | 18.11 | 37.28 | 26.72 | 7.56 | 1.19 | 0.17 | 45
45–54 | 4,562 | 12.75 | 2.08 | 0.26 | 0.81 | 1.01 | 2.76 | 7.90 | 21.07 | 35.48 | 23.88 | 5.77 | 0.94 | * | 5
Hispanic^4^ | Number | Percent | | | | | | | | | | | | | Number
All ages | 945,200 | 7.92 | 1.26 | 0.13 | 0.47 | 0.66 | 1.52 | 5.14 | 20.19 | 40.84 | 24.79 | 5.47 | 0.70 | 0.09 | 493
Younger than 15 | 800 | 12.77 | 2.75 | * | * | 1.88 | 2.00 | 8.01 | 30.54 | 41.68 | 13.27 | 1.75 | * | * | 1
15–19 | 57,914 | 9.15 | 1.37 | 0.14 | 0.55 | 0.68 | 1.62 | 6.16 | 25.93 | 42.92 | 18.78 | 2.89 | 0.29 | 0.04 | 43
20–24 | 207,702 | 7.61 | 1.12 | 0.12 | 0.43 | 0.57 | 1.32 | 5.16 | 21.70 | 42.54 | 23.22 | 4.42 | 0.47 | 0.05 | 122
25–29 | 270,317 | 7.16 | 1.11 | 0.13 | 0.42 | 0.57 | 1.36 | 4.69 | 19.32 | 41.30 | 25.78 | 5.64 | 0.71 | 0.09 | 122
30–34 | 240,489 | 7.73 | 1.29 | 0.13 | 0.48 | 0.68 | 1.52 | 4.92 | 18.76 | 39.90 | 26.29 | 6.37 | 0.84 | 0.11 | 125
35–39 | 131,623 | 8.94 | 1.49 | 0.13 | 0.57 | 0.80 | 1.85 | 5.60 | 19.34 | 38.75 | 25.58 | 6.30 | 0.97 | 0.13 | 63
40–44 | 34,043 | 10.51 | 1.91 | 0.13 | 0.66 | 1.12 | 2.23 | 6.38 | 21.10 | 38.26 | 23.67 | 5.49 | 0.84 | 0.14 | 15
45–54 | 2,312 | 16.49 | 2.99 | * | 1.30 | 1.56 | 4.29 | 9.22 | 23.77 | 35.93 | 19.13 | 4.29 | * | * | 2

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Equivalents of gram weights in pounds and ounces are shown in the User Guide; see reference 9 in this report.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 24 Twin, triplet, and higher-order multiple births: United States, 2010–2023, and by race and Hispanic origin of mother: United States, 2016–2023

Race and Hispanic origin and year | Total | Twin | Triplet and higher-order^1^ | Multiple birth rate | Twin birth rate | Triplet and higher-order birth rate^1^
All races and origins^2^ | Number | | | Rate per 1,000 | | Rate per 100,000
2023 | 3,596,017 | 110,393 | 2,653 | 31.4 | 30.7 | 73.8
2022 | 3,667,758 | 114,483 | 2,895 | 32.0 | 31.2 | 78.9
2021 | 3,664,292 | 114,161 | 2,933 | 32.0 | 31.2 | 80.0
2020 | 3,613,647 | 112,437 | 2,875 | 31.9 | 31.1 | 79.6
2019 | 3,747,540 | 120,291 | 3,286 | 33.0 | 32.1 | 87.7
2018 | 3,791,712 | 123,536 | 3,525 | 33.5 | 32.6 | 93.0
2017 | 3,855,500 | 128,310 | 3,917 | 34.3 | 33.3 | 101.6
2016 | 3,945,875 | 131,723 | 4,003 | 34.4 | 33.4 | 101.4
2015 | 3,978,497 | 133,155 | 4,123 | 34.5 | 33.5 | 103.6
2014 | 3,988,076 | 135,336 | 4,526 | 35.1 | 33.9 | 113.5
2013 | 3,932,181 | 132,324 | 4,700 | 34.8 | 33.7 | 119.5
2012 | 3,952,841 | 131,024 | 4,919 | 34.4 | 33.1 | 124.4
2011 | 3,953,590 | 131,269 | 5,417 | 34.6 | 33.2 | 137.0
2010 | 3,999,386 | 132,562 | 5,503 | 34.5 | 33.1 | 137.6
Non-Hispanic, single race^3^
Black:
2023 | 491,494 | 20,347 | 535 | 42.5 | 41.4 | 108.9
2022 | 511,439 | 21,163 | 556 | 42.5 | 41.4 | 108.7
2021 | 517,889 | 21,047 | 424 | 41.5 | 40.6 | 81.9
2020 | 529,811 | 21,554 | 521 | 41.7 | 40.7 | 98.3
2019 | 548,075 | 22,397 | 589 | 41.9 | 40.9 | 107.5
2018 | 552,029 | 22,502 | 658 | 42.0 | 40.8 | 119.2
2017 | 560,715 | 22,982 | 671 | 42.2 | 41.0 | 119.7
2016 | 558,622 | 22,267 | 628 | 41.0 | 39.9 | 112.4
White:
2023 | 1,787,051 | 56,648 | 1,360 | 32.5 | 31.7 | 76.1
2022 | 1,840,739 | 59,969 | 1,549 | 33.4 | 32.6 | 84.2
2021 | 1,887,656 | 61,438 | 1,762 | 33.5 | 32.5 | 93.3
2020 | 1,843,432 | 60,082 | 1,664 | 33.5 | 32.6 | 90.3
2019 | 1,915,912 | 64,011 | 1,865 | 34.4 | 33.4 | 97.3
2018 | 1,956,413 | 67,203 | 1,996 | 35.4 | 34.4 | 102.0
2017 | 1,992,461 | 70,704 | 2,324 | 36.7 | 35.5 | 116.6
2016 | 2,056,332 | 73,425 | 2,502 | 36.9 | 35.7 | 121.7
Hispanic^4^
2023 | 945,200 | 22,954 | 535 | 24.9 | 24.3 | 56.6
2022 | 937,421 | 22,992 | 575 | 25.1 | 24.5 | 61.3
2021 | 885,916 | 21,401 | 554 | 24.8 | 24.2 | 62.5
2020 | 866,713 | 20,709 | 488 | 24.5 | 23.9 | 56.3
2019 | 886,467 | 21,811 | 590 | 25.3 | 24.6 | 66.6
2018 | 886,210 | 21,654 | 573 | 25.1 | 24.4 | 64.7
2017 | 898,764 | 22,041 | 614 | 25.2 | 24.5 | 68.3
2016 | 918,447 | 22,625 | 538 | 25.2 | 24.6 | 58.6

1 Triplet, quadruplet, quintuplet, and higher-order multiple deliveries.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Table 25 Births, by plurality and age and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin and age of mother | Total | Singleton | Twins | Triplet and higher-order^1^ | Multiple birth rate | Twin birth rate | Triplet and higher-order birth rate^1^
All races and origins^2^ | Number | | | | Rate per 1,000 | | Rate per 100,000
All ages | 3,596,017 | 3,482,971 | 110,393 | 2,653 | 31.4 | 30.7 | 73.8
Younger than 15 | 1,766 | 1,739 | 27 | * | 15.3 | 15.3 | *
15–19 | 140,977 | 138,773 | 2,181 | 23 | 15.6 | 15.5 | 16.3
15–17 | 35,714 | 35,232 | 472 | 10 | 13.5 | 13.2 | 28.0
18–19 | 105,263 | 103,541 | 1,709 | 13 | 16.4 | 16.2 | 12.4
20–24 | 616,970 | 602,488 | 14,234 | 248 | 23.5 | 23.1 | 40.2
25–29 | 986,567 | 956,893 | 29,009 | 665 | 30.1 | 29.4 | 67.4
30–34 | 1,098,052 | 1,060,074 | 37,077 | 901 | 34.6 | 33.8 | 82.1
35–39 | 604,631 | 581,686 | 22,377 | 568 | 37.9 | 37.0 | 93.9
40–44 | 136,333 | 131,527 | 4,638 | 168 | 35.3 | 34.0 | 123.2
45–54 | 10,721 | 9,791 | 850 | 80 | 86.7 | 79.3 | 746.2
Non-Hispanic, single race^3^
Black:
All ages | 491,494 | 470,612 | 20,347 | 535 | 42.5 | 41.4 | 108.9
Younger than 15 | 486 | 480 | * | * | * | * | *
15–19 | 28,414 | 27,801 | 603 | 10 | 21.6 | 21.2 | 35.2
15–17 | 8,011 | 7,896 | 108 | * | 14.4 | 13.5 | *
18–19 | 20,403 | 19,905 | 495 | * | 24.4 | 24.3 | *
20–24 | 103,077 | 99,489 | 3,538 | 50 | 34.8 | 34.3 | 48.5
25–29 | 131,705 | 125,927 | 5,658 | 120 | 43.9 | 43.0 | 91.1
30–34 | 131,500 | 125,295 | 6,080 | 125 | 47.2 | 46.2 | 95.1
35–39 | 74,492 | 70,974 | 3,419 | 99 | 47.2 | 45.9 | 132.9
40–44 | 19,925 | 19,036 | 820 | 69 | 44.6 | 41.2 | 346.3
45–54 | 1,895 | 1,610 | 223 | 62 | 150.4 | 117.7 | 3,271.8
White:
All ages | 1,787,051 | 1,729,043 | 56,648 | 1,360 | 32.5 | 31.7 | 76.1
Younger than 15 | 351 | 344 | * | * | * | * | *
15–19 | 44,922 | 44,285 | 631 | * | 14.2 | 14.0 | *
15–17 | 9,229 | 9,101 | 125 | * | 13.9 | 13.5 | *
18–19 | 35,693 | 35,184 | 506 | * | 14.3 | 14.2 | *
20–24 | 263,760 | 257,802 | 5,846 | 112 | 22.6 | 22.2 | 42.5
25–29 | 500,910 | 485,649 | 14,876 | 385 | 30.5 | 29.7 | 76.9
30–34 | 595,741 | 574,592 | 20,640 | 509 | 35.5 | 34.6 | 85.4
35–39 | 314,198 | 301,702 | 12,201 | 295 | 39.8 | 38.8 | 93.9
40–44 | 62,607 | 60,388 | 2,169 | 50 | 35.4 | 34.6 | 79.9
45–54 | 4,562 | 4,281 | 278 | * | 61.6 | 60.9 | *
Hispanic^4^
All ages | 945,200 | 921,711 | 22,954 | 535 | 24.9 | 24.3 | 56.6
Younger than 15 | 800 | 788 | 12 | * | 15.0 | 15.0 | *
15–19 | 57,914 | 57,133 | 774 | * | 13.5 | 13.4 | *
15–17 | 15,880 | 15,678 | 202 | * | 12.7 | 12.7 | *
18–19 | 42,034 | 41,455 | 572 | * | 13.8 | 13.6 | *
20–24 | 207,702 | 203,808 | 3,829 | 65 | 18.7 | 18.4 | 31.3
25–29 | 270,317 | 263,947 | 6,267 | 103 | 23.6 | 23.2 | 38.1
30–34 | 240,489 | 233,552 | 6,734 | 203 | 28.8 | 28.0 | 84.4
35–39 | 131,623 | 127,318 | 4,188 | 117 | 32.7 | 31.8 | 88.9
40–44 | 34,043 | 33,047 | 968 | 28 | 29.3 | 28.4 | 82.2
45–54 | 2,312 | 2,118 | 182 | 12 | 83.9 | 78.7 | 519.0

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Triplet, quadruplet, quintuplet, and higher-order multiple deliveries.

2 Includes births to race and origin groups not shown separately, such as Hispanic single-race Black, Hispanic single-race White, and non-Hispanic multiple-race women, as well as births with origin not stated.

3 Race groups are single race. Race and Hispanic origin are reported separately on birth certificates. In this table, non-Hispanic women are classified by race. Race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the birth certificate.

4 Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statsitics, National Vital Statistics System, natality data file.

### Period of gestation

The U.S. preterm birth rate was essentially unchanged in 2023 at 10.41% compared with 10.38% in 2022. The preterm birth rate (percentage of all births delivered at less than 37 completed weeks of gestation) declined steadily from 2007 (10.44%) to 2014 (9.57%) (12), rose 7% through 2019 (10.23%), and fluctuated from 2019 to 2022 (Table 20). (National data based on the obstetric estimate of gestation are available only from 2007 [23]; see Technical Notes.)

No change from 2022 to 2023 was seen among infants born early preterm (less than 34 weeks) (2.76%); the change in the rate of late preterm births (34–36 weeks) was not significant (7.62% to 7.64%). Both early and late preterm rates rose 4% from 2020 to 2021 but declined 1%–2% from 2021 to 2022.The late preterm birth rates for 2021–2023 are the highest since comparable data have been available (2007) (12,23,24).

Changes in the distribution of births delivered at term and later (37 weeks and higher) were also observed from 2022 to 2023. Following trends generally observed since 2014 (24), the percentage of infants born early term (37–38 weeks) rose 2% in 2023, from 29.31% to 29.84%, while full-term births (39–40 weeks) declined 1% (55.32% to 54.94%). Late-term births (41 weeks) declined 4% (4.73% to 4.56%), and the percentage of post-term births (42 weeks and higher) (0.26%) was unchanged. From 2007 to 2014, the early-term birth rate had generally declined, and the full-term rate had increased (12). The percentage of post-term births generally declined from 2007 to 2019 but was unchanged at 0.25% to 0.26% for 2019–2023 (Table 20) (12). Increases in early-term and declines in full- and late-term births were seen for the three largest race and Hispanic-origin groups from 2022 to 2023 (the decline in full-term births for Hispanic mothers was not significant).

Preterm birth rates did not change significantly for the largest race and Hispanic-origin groups from 2022 to 2023: Black (14.59% to 14.65%), White (9.44%), and Hispanic (10.06% to 10.14%) mothers (Table 20). For 2023, preterm birth rates for race and Hispanic-origin groups ranged from a high of 14.65% for births to Black mothers to a low of 9.08% among Asian mothers (Table 13). Preterm rates for Hispanic subgroups ranged from 9.55% (Central and South American) and 9.76% (Cuban) to 11.81% (Puerto Rican) (Table 14).

Analyzing births in singleton deliveries separately from all births can also be important because of the shorter average gestations of multiple births and their corresponding potential influence on preterm birth rates (see also “Multiple births” in this report). The 2023 preterm birth rate for singleton births only was 8.71%, less than a 1% increase from the 2022 rate of 8.67% (see Table B for 2023 data) (15). From 2007 to 2014, the singleton preterm rate declined from 8.59% to 7.74%, but it has risen 13% from 2014 to 2023 (12,25).

Table B Gestational age and birthweight characteristics, by plurality: United States, 2023

Plurality | Number of births | Early preterm^1^ | Preterm^2^ | Very low birthweight^3^ | Low birthweight^4^
| | Percent
All births | 3,596,017 | 2.76 | 10.41 | 1.36 | 8.58
Singleton | 3,482,971 | 2.17 | 8.71 | 1.08 | 7.00
Twin | 110,393 | 19.95 | 61.88 | 9.37 | 56.27
Triplet | 2,505 | 67.49 | 98.72 | 34.45 | 95.10
Quadruplet | 128 | 96.09 | 99.22 | 82.26 | 98.39
Quintuplet and higher-order multiples | 20 | 75.00 | 90.00 | 70.00 | 90.00

1 Less than 34 completed weeks of gestation.

2 Less than 37 completed weeks of gestation.

3 Less than 1,500 grams (3 lb 4 oz).

4 Less than 2,500 grams (5 lb 8 oz).

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Preterm birth rates declined in four states from 2022 to 2023 (Colorado, Kentucky, Vermont, and Wisconsin), and increased in two states (South Dakota and Tennessee); changes in other states were not significant. See Table XV for 2023 data.

### Birthweight

The percentage of infants born low birthweight (LBW; less than 2,500 grams or 5 pounds, 8 ounces) was 8.58% in 2023, a nonsignificant decline from 2022 (8.60%) (Tables 22 and 23). While fluctuating somewhat over the last 4 decades, the rate has risen more than 20% since the 1980s and is up 7% since the most recent low in 2012 (7.99%) (12).

The 2023 very low birthweight rate (less than 1,500 grams) was unchanged from 2022 at 1.36%. The very low birthweight rate is down from the high of 1.49% for 2005–2007 (12). The percentage of moderately low birthweight infants (1,500–2,499 grams) was 7.22% compared with 7.24% in 2022; moderately low birthweight levels for 2016–2023 have matched or surpassed the peak reported for 2006 (6.77%) (Table 22) (12).

From 2022 to 2023, the LBW rate declined among births to White women (from 7.12% to 7.04%); increases for Black (14.75% to 14.80%) and Hispanic (7.87% to 7.92%) women were not significant. Since 2016, LBW rates have fluctuated for all groups but have increased a total of 1% for White women (from 6.97%) and 8% for both Black (13.68%) and Hispanic (7.32%) women (Table 22). See Tables 13, 14, XVII, and XVIII for 2023 very low birthweight and LBW rates by state and race and Hispanic origin.

The LBW rate among singleton births only was essentially unchanged at 7.00% in 2023 compared with 7.01% in 2022 (15); see Table B for 2023 data. Examining births in singleton deliveries separately can be informative because multiple births tend to be born smaller than singleton births, and changes in multiple-birth incidence can influence overall LBW levels.

### Multiple births

The 2023 twin birth rate was 30.7 twins per 1,000 births, a 2% decline from the 2022 rate of 31.2 (Tables 24 and 25) and the lowest rate reported in more than 20 years (12) (Figure 4). The twinning rate (births in twin deliveries per 1,000 total births) rose 76% from 1980 to 2009 (from 18.9 to 33.2 per 1,000), was generally stable from 2009 to 2012, and then rose for 2013 and 2014 before declining 8% from 2014 to 2020 (12).

Figure 4 Twin birth rate: United States, 2014–2023

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 4 is a line graph showing the twin birth rate in the United States, 2014–2023.

The triplet and higher-order multiple birth rate (triplet/+) was 73.8 per 100,000 births for 2023, a 6% decline from 2022 (78.9) (Tables 24 and 25). The 2023 rate of triplet/+ births is down 62% from the 1998 peak (193.5) (12). The triplet/+ birth rate (number of triplets, quadruplets, and quintuplet and higher-order multiples per 100,000 births) rose more than 400% from 1980 to 1998 (12).

A total of 110,393 infants were born in twin deliveries in 2023, down 4% from the 114,483 twins reported in 2022 (Table 24). The number of infants born in triplet/+ deliveries declined 8% in 2023 to 2,653 births, from 2,895 in 2022. The number of triplet/+ births is down 65% since the 2003 high when 7,663 triplet/+ births were reported (12). The 2023 number included 2,505 triplets, 128 quadruplets, and 20 quintuplet and higher-order multiple births. See Table B for the number of births and percentages of preterm and LBW births by plurality.

Twin birth rates were unchanged from 2022 to 2023 for Black (41.4) and Hispanic (24.5 to 24.3) women but declined 3% for White women (32.6 to 31.7). Triplet/+ birth rates were also essentially unchanged for Black (108.7 to 108.9) and Hispanic (61.3 to 56.6) women from 2022 to 2023 but declined 10% for White women (84.2 to 76.1) (Table 24; also see Tables 13 and 14 for 2023 twin and triplet/+ rates for additional race and Hispanic-origin groups). For state-specific twin and triplet/+ rates, see Table XIX.

## Technical Notes

### Data source

Data shown in this report for 2023 are based on 100% of the birth certificates filed in all states and the District of Columbia (D.C.). The data are provided to the National Center for Health Statistics (NCHS) through the Vital Statistics Cooperative Program. Information on the percentage of records with missing information for maternal and infant characteristics included in this report is shown by state in the “User Guide to the 2023 Natality Public Use File” (9); methodological and measurement information for these characteristics is also available in the 2023 User Guide.

#### 2003 revision of U.S. Standard Certificate of Live Birth

Data for 2016–2023 presented in this report are based on the 2003 revision of the U.S. Standard Certificate of Live Birth; data for 2010–2015 are based on both the 1989 and 2003 birth certificate revisions. The 2003 revision is described in detail elsewhere (26).

#### Additional data tables

Data on several additional topics, such as birth by attendant and place of delivery, mean age of mother by live-birth order, maternal prepregnancy body mass index, infections during pregnancy, and maternal morbidity, are presented in Tables I–XXI. In previous reports, these tables were supplemental and were published separately from reports.

### Age of mother

Age of mother is computed in most cases from the mother’s and infant’s dates of birth as reported on the birth certificate. Since 2007, age of mother has been imputed for age 8 and younger and age 65 and older. Mothers age 9 are recoded as age 10. A review and verification of unedited data for several years including 2007 showed that most births reported as occurring to women age 50 and older were to women ages 50–54. In this report, the final age group shown in the tables (45–49, 45–54, or 50–54) includes births to mothers up to age 64. For historical information on mother’s age, see the 2023 User Guide (9).

### Marital status

Due to state statutory restrictions, beginning in 2017, California no longer provides record-level data on the marital status of the mother for births occurring in, or to residents of, the state. Instead of record-level data, California provides to NCHS counts of births by marital status category (married, unmarried, and unknown) by age and race and Hispanic origin of the mother according to the age and race and Hispanic-origin categories shown in this report. For consistency with procedures for handling missing information for other jurisdictions, California’s counts of birth by marital status were redistributed (proportionately) to the same maternal age, race, and marital status subgroups in the data set to obtain the national estimates by marital status. This approach is consistent with hot-deck procedures used for non-California records to impute missing information for age, race, and marital status based on records for which these characteristics are known.

### Hispanic origin and race

#### Hispanic origin

Hispanic origin and race are reported separately on the birth certificate. Data are shown in most cases for five specified Hispanic groups: Central and South American, Cuban, Dominican, Mexican, and Puerto Rican, as well as other and unknown Hispanic. Before 2018, data for the Dominican subgroup had been included in the category of other and unknown Hispanic. In tabulations of birth data by race and Hispanic origin, data for people of Hispanic origin are not further classified by race because most births to Hispanic women are reported as White. Starting with 2023, data for Central and South American no longer include Latin American, which has been moved to other and unknown Hispanic to conform with the U.S. Census Bureau (9).

Items asking for the Hispanic origin of the mother (and the father) have been included on the birth certificates of all states, D.C., U.S. Virgin Islands, and Guam since 1993, and on the birth certificates of Puerto Rico starting in 2005 and Commonwealth of the Northern Marianas (Northern Marianas) starting in 2010 (9,12). American Samoa does not collect information on Hispanic origin.

The Hispanic-origin question on the 2003 revision of the birth certificate asks respondents to select only one response. Occasionally, however, more than one Hispanic-origin response is given (that is, a specified Hispanic group [Central and South American, Cuban, Dominican, Mexican, or Puerto Rican] in combination with one or more other specified Hispanic group). From 2003 to 2012, respondents who selected more than one Hispanic origin on the birth certificate were classified as “other Hispanic.” Beginning with the 2013 data year, respondents who select more than one Hispanic origin are randomly assigned to a single Hispanic origin. This change was implemented to be consistent with the coding methods of the American Community Survey (27), on which the rates for the specified Hispanic groups from 2020 are based (see “Population estimates for specific Hispanic groups”).

#### Race

This report presents data on race and Hispanic origin based on the 1997 Office of Management and Budget (OMB) standards (11). The 2003 revision of the U.S. Standard Certificate of Live Birth allows the reporting of five race categories either alone (single race) or in combination (more than one race or multiple races) for each parent (10), according to the revised standards issued by OMB in 1997 (11). The five categories for race specified in the revised standards are: American Indian and Alaska Native, Asian, Black or African American, Native Hawaiian and Other Pacific Islander, and White; see the 2023 User Guide (9).

Beginning in 2016, all states and D.C., in addition to Puerto Rico, U.S. Virgin Islands, Guam, and Northern Marianas, were reporting race according to the 1997 revised OMB standards, with 3.0% of mothers in the United States reporting more than one race in 2023 (9). Before 2016, the multiple-race reporting states varied widely, increasing from 6 states in 2003 to all 50 states, D.C., and all territories except American Samoa in 2016.

### Gestational age

Beginning with the 2014 data year, NCHS transitioned to a new standard for estimating the gestational age of the newborn. The new measure—the obstetric estimate of gestation at delivery —replaces the measure based on the date of the last normal menses (23). National data based on the obstetric estimate are available only from data year 2007 forward. Gestational age estimates differ somewhat between the obstetric estimate- and last normal menses-based measures. Accordingly, gestational age data in this report are based on the obstetric estimate. Information and discussion of the reasons for the change, and a detailed comparison of the two measures, are presented elsewhere (23).

### Computations of rates, percentages, percent distributions, and means

For information and discussion on computations of rates, percentages, percent distributions, and means, see the 2023 User Guide (9). Births for which a particular characteristic is unknown were subtracted from the counts for total births used as denominators before percentages, percentage distributions, and means were computed. The mean age of mother is the arithmetic average of the age of mothers at the time of birth, computed directly from the frequency of births by age of mother.

### Population denominators

The birth and fertility rates for 2022 shown in Tables 1, 2, 5, 8, 10, and 11 are estimated as of July 1, 2023, based on the blended base population estimates produced by the Census Bureau instead of the April 1, 2020, decennial population count. The blended base consists of the blend of 2020 census data, 2020 demographic analysis estimates, and vintage 2020 estimates (28,29). These populations are shown in the 2023 User Guide (9). The population estimates provided by the Census Bureau (30) are presented by age, sex, and race. The race categories are consistent with the revised 1997 OMB standards (11).

The birth and fertility rates by state shown in Table 8 are based on state population counts, which are based on the blended base population estimates provided by the Census Bureau (30). Birth and fertility rates for the territories except Puerto Rico shown in Table 8 are based on population estimates provided by the Census Bureau’s International Data Base (31). Rates for Puerto Rico are based on estimates developed from a base that integrates the 2020 census data and vintage 2020 estimates as of July 1, 2023, and are provided by the Census Bureau (32).

Rates by state and territory shown in this report may differ from rates computed based on other population estimates; rates for smaller population subgroups, such as those for teen mothers, may be particularly affected by differences in population estimates. For 2023, rates for unmarried women shown in Tables 10 and 11 are based on distributions of the population by marital status averaged over a 2-year period for 2022–2023. These distributions were reported by the Census Bureau in the March Current Population Survey for each year (33,34) and have been adjusted to July 1, 2023, (blended base) population levels (30) by NCHS’s Division of Vital Statistics (35).

The population distributions by marital status are based on a 2-year average (of the current and previous year) from 2022 to 2023 (12). For earlier years, rates for unmarried females are based on distributions of the population by marital status averaged over a 3-year period (35).

Birth and fertility rates for 2020 have been revised and may differ from those published in “Births: Final Data for 2020” and elsewhere (14). Previously published birth and fertility rates for 2020 were based on postcensal population estimates derived from the 2010 census. The revised rates shown in this report are based on population estimates consistent with the blended base as of April 1. When the intercensal population estimates for 2011–2019 based on the blended base population estimates become available, revised birth and fertility rates for 2011–2019 will be presented in a separate report.

### Population estimates for specific Hispanic groups

The 2023 population estimates for the specific Hispanic population groups were not available when this report was being prepared (36). Accordingly, birth and fertility rates for these groups for 2023 are not shown in this report. Once available, birth and fertility rates for the specific Hispanic population groups will be published.

### Presentation of counts, rates, and percentages

An asterisk (*) in the tables indicates that a count, rate, or percentage does not meet NCHS standards of reliability (37,38). Two separate criteria are used to determine if a count (number of events), rate, or proportion meets these standards (9).

#### Presentation of counts and rates

New criteria for showing counts and rates (based on a population denominator from a decennial census or postcensal or intercensal population estimate) were adopted by NCHS beginning with 2023 data (37). The number of births or a rate is shown depending on the count of births (by itself or as the numerator of the rate) and on the relative width of the confidence interval of the count, based on a gamma distribution. For rates based on population estimates from the Current Population Survey (CPS) or the American Community Survey (ACS), a rate is shown depending on the count for the numerator and on the relative width of the confidence interval of the numerator of the rate based on a Student’s t interval for the logarithm of the rate (with the variance estimated using a method supplied with CPS data). Rates published for data years before 2023 are represented by an asterisk when the numerator is fewer than 20 births; the number of births is shown regardless of the count. For detailed information on the new criteria, see “National Center for Health Statistics Data Presentation Standards for Proportions” (37).

#### Presentation of percentages

For proportions (or percentages), new criteria were adopted by NCHS beginning with 2017 data, and an additional criterion was added in 2023 (38). For 2017 and later, a proportion (percentage) is shown based on the denominator size and on the absolute or relative widths of the confidence interval of the proportion or percentage calculated using the Clopper–Pearson method. For the presentation criterion used before the 2017 data year, see the 2023 User Guide (9). Starting in 2023, proportions or percentages based on fewer than 10 births are represented with an asterisk. For detailed information on these criteria, see “National Center for Health Statistics Data Presentation Standards for Proportions” (38).

### Random variation and significance testing for natality data

For information and discussion on random variation and significance testing for natality data, see the 2010 User Guide (39).

For information and discussion on random variation and significance testing for birth and fertility rates for Central and South American, Cuban, Dominican, Mexican, Puerto Rican, and other Hispanic populations based on ACS population estimates, see the 2023 User Guide (9).

### Definitions of medical terms

For definitions and discussion of medical and health items presented in this report, see “Guide to Completing the Facility Worksheets for the Certificate of Live Birth and Report of Fetal Death” (40).

## Acknowledgments

This report was prepared in the Division of Vital Statistics under the general direction of Director Paul Sutton; Robert Anderson, Chief, Statistical Analysis and Surveillance Branch; and Joyce Martin, Team Leader, Perinatal Research and Statistics Team, Statistical Analysis and Surveillance Branch. Rajesh Virkar, Chief of the Systems, Programming, and Statistical Resources Branch, and Steve J. Steimel and Annie S. Liu, Systems, Programming, and Statistical Resources Branch, provided computer programming support and statistical tables. Steve J. Steimel and Annie S. Liu also prepared the natality file. Data Acquisition and Evaluation Branch staff evaluated the quality of and acceptance procedures for the state data files on which this report is based. The National Center for Health Statistics Office of Information Services, Information Design and Publishing Staff edited and produced this report: editor Laura Drescher, typesetter and graphic designer Odell D. Eldridge (contractor), and typesetter Michael W. Jones (contractor).

## References

1 Hamilton BE, Martin JA, Osterman MJK. Births: Provisional data for 2023. Vital Statistics Rapid Release; no 35. Hyattsville, MD: National Center for Health Statistics. April 2024. DOI: 10.15620/cdc/151797.
2 National Center for Health Statistics. Provisional estimates for selected maternal and infant outcomes by month, 2019–2023. Available from: https://www.cdc.gov/nchs/covid19/technical-notes-outcomes.htm.
3 Martin JA, Hamilton BE, Osterman MJK. Births in the United States, 2023. NCHS Data Brief, no 507. Hyattsville, MD: National Center for Health Statistics. 2024. DOI: 10.15620/cdc/158789.
4 National Center for Health Statistics. Vital statistics online data portal. Birth data files. Available from: https://www.cdc.gov/nchs/data_access/VitalStatsOnline.htm.
5 National Center for Health Statistics. Data release policy for vital statistics micro-data files. Available from: https://www.cdc.gov/nchs/nvss/dvs_data_release.htm.
6 Centers for Disease Control and Prevention. CDC WONDER. Natality information: Live births. Available from: https://wonder.cdc.gov/natality.html.
7 Martin JA, Wilson EC, Osterman MJK, Saadi EW, Sutton SR, Hamilton BE. Assessing the quality of medical and health data from the 2003 birth certificate revision: Results from two states. National Vital Statistics Reports; vol 62 no 2. Hyattsville, MD: National Center for Health Statistics. 2013.
8 Gregory ECW, Martin JA, Argov EL, Osterman MJK. Assessing the quality of medical and health data from the 2003 birth certificate revision: Results from New York City. National Vital Statistics Reports; vol 68 no 8. Hyattsville, MD: National Center for Health Statistics. 2019.
9 National Center for Health Statistics. User guide to the 2023 natality public use file. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2023.pdf.
10 National Center for Health Statistics. 2003 revisions of the U.S. standard certificates and reports. Available from: https://www.cdc.gov/nchs/nvss/vital_certificate_revisions.htm.
11 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist 62(210):58782–90. 1997.
12 Martin JA, Hamilton BE, Osterman MJK, Driscoll AK, Mathews TJ. Births: Final data for 2015. National Vital Statistics Reports; vol 66 no 1. Hyattsville, MD: National Center for Health Statistics. 2017. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr66/nvsr66_01.pdf.
13 Martin JA, Hamilton BE, Osterman MJK, Driscoll AK, Drake P. Births: Final data for 2016. National Vital Statistics Reports; vol 67 no 1. Hyattsville, MD: National Center for Health Statistics. 2018. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr67/nvsr67_01.pdf.
14 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2020. National Vital Statistics Reports; vol 70 no 17. Hyattsville, MD: National Center for Health Statistics. 2022. DOI: 10.15620/cdc:112078.
15 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2022. National Vital Statistics Reports; vol 73, no 2. Hyattsville, MD: National Center for Health Statistics. 2024. DOI: 10.15620/cdc:145588.
16 National Center for Health Statistics. Vital statistics of the United States, 2003, Volume I, Natality. Available from: https://www.cdc.gov/nchs/products/vsus/vsus_1980_2003.htm.
17 Ventura SJ, Hamilton BE, Mathews TJ. National and state patterns of teen births in the United States, 1940– 2013. National Vital Statistics Reports; vol 63 no 4. Hyattsville, MD: National Center for Health Statistics. 2014. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr63/nvsr63_04.pdf.
18 Hamilton BE, Rossen LM, Branum AM. Teen birth rates for urban and rural areas in the United States, 2007– 2015. NCHS Data Brief, no 264. Hyattsville, MD: National Center for Health Statistics. 2016. Available from: https://www.cdc.gov/nchs/data/databriefs/db264.pdf.
19 Martin JA, Osterman MJK, Driscoll AK. Declines in cigarette smoking during pregnancy in the United States, 2016– 2021. NCHS Data Brief, no 458. Hyattsville, MD: National Center for Health Statistics. 2023. DOI: 10.15620/cdc:123360.
20 Martin JA. Osterman MJK. Changes in prenatal care utilization: United States, 2019–2021. National Vital Statistics Reports; vol 72 no 4. Hyattsville, MD: National Center for Health Statistics. 2023. DOI: 10.15620/cdc:125706.
21 Osterman MJK. Changes in primary and repeat cesarean delivery: United States, 2016–2021. Vital Statistics Rapid Release; no 21. Hyattsville, MD: National Center for Health Statistics. July 2022. DOI: 10.15620/cdc:117432.
22 Valenzuela CP, Osterman MJK. Characteristics of mothers by source of payment for the delivery: United States, 2021. NCHS Data Brief, no 468. Hyattsville, MD: National Center for Health Statistics. 2023. DOI: 10.15620/cdc:127266.
23 Martin JA, Osterman MJK, Kirmeyer SE, Gregory ECW. Measuring gestational age in vital statistics data: Transitioning to the obstetric estimate. National Vital Statistics Reports; vol 64 no 5. Hyattsville, MD: National Center for Health Statistics. 2015.
24 Martin JA, Osterman MJK. Shifts in the distribution of births by gestational age: United States, 2014– 2022. National Vital Statistics Reports; vol 73 no 1. Hyattsville, MD: National Center for Health Statistics. 2024. DOI: 10.15620/cdc:135610.
25 Hamilton BE, Martin JA, Osterman MJK, Curtin SC, Mathews TJ. Births: Final data for 2014. National Vital Statistics Reports; vol 64 no 12. Hyattsville, MD: National Center for Health Statistics. 2015.
26 National Center for Health Statistics. Report of the Panel to Evaluate the U.S. Standard Certificates. 2000.
27 Ramirez RR, Ennis SR. Item nonresponse, allocation, and data editing of the question on Hispanic origin in the American Community Survey (ACS): 2000 to 2007. U.S. Census Bureau. Working Paper no 86. 2010.
28 U.S. Census Bureau. Vintage 2023 release notes: 2024. Available from: https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2023/2023-est-relnotes.pdf.
29 U.S. Census Bureau. Methodology for the United States population estimates: Vintage 2023. Nation, states, counties, and Puerto Rico–April 1, 2020 to July 1, 2023. 2024. Available from: https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2023/methods-statement-v2023.pdf.
30 U.S. Census Bureau. State population by characteristics: 2020–2024. Datasets: Annual state resident population estimates for 6 race groups (5 race alone groups and two or more races) by age, sex, and Hispanic origin: April 1, 2020 to July 1, 2023 (SC-EST2023-ALLDATA6). 2024. Available from: https://www.census.gov/data/datasets/time-series/demo/popest/2020s-state-detail.html.
31 U.S. Census Bureau. International data base. Population by single years of age and sex, 2023. 2024. Available from: https://www.census.gov/data-tools/demo/idb/#/dashboard?dashboard_page=country&COUNTRY_YR_ANIM=2023&COUNTRY_YEAR=2023.
32 U.S. Census Bureau. 2023 population estimates. Annual estimates of the resident population by single year of age and sex for the Puerto Rico Commonwealth: April 1, 2020 to July 1, 2023 (PRCEST2023-SYASEX). 2024. Available from: https://www2.census.gov/programs-surveys/popest/tables/2020-2023/puerto-rico/asrh/prc-est2023-syasex.xlsx.
33 U.S. Census Bureau. Microdata access tool. Current Population Survey. 2022 March >Annual Social and Economic Supplement. 2023. Available from: https://data.census.gov/app/mdat/CPSASEC2022.
34 U.S. Census Bureau. Microdata access tool. Current Population Survey. 2023 March Annual Social and Economic Supplement. 2024. Available from: https://data.census.gov/app/mdat/CPSASEC2023.
35 Ventura SJ, Bachrach CA. Nonmarital childbearing in the United States, 1940–99. National Vital Statistics Reports; vol 48 no 16. Hyattsville, MD: National Center for Health Statistics. 2000.
36 U.S. Census Bureau. American Community Survey (ACS), 2023 1-year estimates (st31002_2023_010_flags), by sex, age, nativity, and Hispanic origin. Population estimates for 2024 based on unpublished tabulations. [Forthcoming].
37 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D, et al. National Center for Health Statistics data presentation standards for rates and counts. National Center for Health Statistics. Vital Health Stat 2(200). 2023. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02-200.pdf.
38 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. National Center for Health Statistics. Vital Health Stat 2(175). 2017. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_175.pdf.
39 National Center for Health Statistics. User guide to the 2010 natality public use file. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2010.pdf.
40 National Center for Health Statistics. Guide to completing the facility worksheets for the certificate of live birth and report of fetal death (2003 revision). 2022 update. Available from: https://www.cdc.gov/nchs/data/dvs/GuidetoCompleteFacilityWks.pdf.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/.

For questions or general information about NCHS: Tel: 1–800–CDC–INFO (1–800–232–4636) • TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs • Online request form: https://www.cdc.gov/info