# Volume 74, Number 8 Fetal Mortality: United States, 2023

### Objectives

This report presents 2023 fetal mortality data by maternal race and Hispanic origin, age, tobacco use during pregnancy, and state of residence, as well as by plurality, sex, gestational age, birthweight, and selected causes of death. Trends in fetal mortality are also examined.

### Methods

Descriptive tabulations of data are presented and interpreted for all fetal deaths reported for the United States for 2023 with a stated or presumed period of gestation of 20 weeks or more. Cause-of-fetal-death data only are restricted to residents of the 38 states and District of Columbia where cause of death was based on the 2003 fetal death report revision for the full year and less than 50% of deaths were attributed to Fetal death of unspecified cause (P95).

### Results

A total of 20,005 fetal deaths at 20 weeks of gestation or more were reported in the United States in 2023. The 2023 U.S. fetal mortality rate was 5.53 fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths, not significantly different from the rate of 5.48 in 2022. The fetal mortality rate in 2023 for deaths occurring at 20–27 weeks of gestation was 2.89, a 4% increase from 2022 (2.79). For deaths occurring at 28 weeks of gestation or more, the rate in 2023 (2.66) was not significantly different from 2022 (2.71). In 2023, the fetal mortality rate was highest for Native Hawaiian or Other Pacific Islander non-Hispanic (10.18) and Black non-Hispanic (9.95) women and lowest for Asian non-Hispanic women (4.14). Fetal mortality rates were highest for females younger than 15 and age 40 and older, for women who smoked during pregnancy, and for women with multiple gestation pregnancies. Five selected causes accounted for 89.9% of fetal deaths in the 38-state and District of Columbia reporting area.

## Introduction

Fetal mortality—the intrauterine death of a fetus at any gestational age—is a major but often overlooked public health issue. Much of the public concern surrounding pregnancy and infant loss has focused on infant mortality, due in part to lesser knowledge of the incidence, causes (etiology), and prevention strategies for fetal mortality. This report presents detailed data on numbers and rates of fetal deaths for the United States for 2023. Data are presented by maternal race and Hispanic origin, age, tobacco use during pregnancy, and state of residence, as well as by plurality, sex, gestational age at delivery, birthweight, and selected causes of death. Trends in fetal mortality are also examined.

In addition to the tabulations included in this report, more detailed analysis of fetal mortality is possible by using the annual fetal death public-use file (available from: https://www.cdc.gov/nchs/data_access/Vitalstatsonline.htm). The public-use file does not include geographic detail; a file with this information may be available upon special request (see the Division of Vital Statistics data release policy at: https://www.cdc.gov/nchs/nvss/dvs_data_release.htm). National and state-level fetal death data may also be accessed via the Centers for Disease Control and Prevention’s WONDER, a web-based data query system that makes CDC data available to public health professionals and the public (1).

## Methods

### Data sources

Data in this report are drawn from two National Center for Health Statistics vital statistics data files: the 2023 fetal death data set (for fetal deaths) and the 2023 birth data set (for births). The 2023 fetal death data set contains information from all reports of fetal death filed in the 50 states, District of Columbia (D.C.), Guam, and Puerto Rico (American Samoa did not report data for 2023, and data for the Commonwealth of the Northern Mariana Islands [subsequently, Northern Marianas] and U.S. Virgin Islands were excluded to protect confidentiality due to the small number of events reported) (2). The 2023 birth data set contains information from all U.S. Standard Certificates of Live Birth filed in the 50 states, D.C., Guam, Northern Marianas, Puerto Rico, and U.S. Virgin Islands (American Samoa did not report data for 2023). Tables showing data by jurisdiction also provide separate information for Guam and Puerto Rico; however, these data are not included in U.S. totals.

### Fetal mortality

Fetal death refers to the intrauterine death of a fetus prior to delivery (Technical Notes). Fetal mortality is generally divided into three periods based on gestational age: less than 20 completed weeks of gestation (commonly referred to as miscarriages), 20–27 weeks of gestation (early fetal deaths), and 28 weeks of gestation or more (late fetal deaths). Although the vast majority of fetal deaths occur early in pregnancy, most U.S. states require the reporting of fetal deaths only at 20 weeks of gestation or more (2), and fetal mortality data from the National Vital Statistics System are usually presented for fetal deaths at 20 weeks of gestation or more. Consequently, only fetal deaths reported at 20 weeks of gestation or more are included in this report. Numbers and rates for early and late fetal deaths are shown separately for selected variables. Statistics on fetal death exclude data for induced terminations of pregnancy. Fetal mortality rates in this report are computed as the number of fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths at 20 weeks or more (Technical Notes). See Technical Notes for new count, rate, and proportion presentation standards.

### Data limitations

Variation exists among states in reporting requirements and possibly in completeness of reporting of fetal death data, and these variations can have implications for data quality and completeness (Technical Notes). Correct interpretation of fetal death data should include an evaluation of the completeness of reporting of fetal deaths, as well as an evaluation of the completeness of reporting for the specific variables of interest (3–5). The percentage of not-stated responses for fetal death data varies markedly among variables and states; see “User Guide to the 2023 Fetal Death Public Use File” (2).

Tobacco use data for Hawaii for 2023 are excluded from tabulations shown in this report due to a high percentage of unknown responses (60.0%).

### 2003 revision of U.S. Standard Report of Fetal Death

Starting in 2018, all 50 states, D.C., Guam, Northern Marianas, Puerto Rico, and U.S. Virgin Islands reported data based on the 2003 U.S. Standard Report of Fetal Death.

Data on items such as mother’s date of birth, race, Hispanic origin, level of education, tobacco use during pregnancy, and place of residence are recommended to come from the mother (see the Patient’s Worksheet [6]). Data on items such as prenatal care, medical risk factors, maternal morbidity, plurality, sex of fetus, gestational age, birthweight, and cause of death are recommended to come from the medical records (see the Facility Worksheet [7]). Detailed definitions for data items that are collected from the Facility Worksheet are in the “Guide to the Facility Worksheet” (8). Further information on fetal death reporting is available in the eLearning training, “Applying Best Practices for Reporting Medical and Health Information on Birth Certificates,” available from: https://www.cdc.gov/nchs/training/BirthCertificateElearning.

This report uses final fetal death data to present information on fetal deaths and fetal death rates by race and Hispanic origin, maternal age, tobacco use during pregnancy, plurality, sex of fetus, gestational age, birthweight, state of residence, and selected causes of death.

### Race and Hispanic origin

The 2003 revision of the U.S. Standard Report of Fetal Death allows the reporting of more than one race (multiple races) for the mother (9), according to the revised standards issued by the Office of Management and Budget in 1997 (10). Starting in 2018, all 50 states and D.C., Guam, Northern Marianas, Puerto Rico, and U.S. Virgin Islands reported race data according to these 1997 standards, which require the reporting of a minimum of five race categories and allow for reporting of race by either single race (reported alone) or in combination (more than one race or multiple races) (10). The race and Hispanic-origin groups shown in this report follow the 1997 standards and differ from the bridged-race categories shown in reports before 2018 (11). The current categories are American Indian and Alaska Native non-Hispanic single race, Asian non-Hispanic single race, Black or African American non-Hispanic single race, Native Hawaiian or Other Pacific Islander non-Hispanic single race, White non-Hispanic single race, and Hispanic (for brevity in text, references to the race groups omit “non-Hispanic single race”).

Race and Hispanic origin are reported independently on the report of fetal death. Most tables in this report show data for the categories of Asian, Black, White, and Hispanic. Selected tables also include data for the categories American Indian and Alaska Native and Native Hawaiian or Other Pacific Islander. Data are also presented in some tables for Hispanic subgroups: Central and South American, Cuban, Dominican, Mexican, other and unknown Hispanic, and Puerto Rican. Data were presented separately for Dominican women for the first time beginning with the 2018 data year. Data for this subgroup had previously been included in the category other and unknown Hispanic.

### Fetal deaths by state

Comparisons of fetal mortality rates by state can be affected by differences in reporting requirements for fetal deaths among registration areas, particularly for fetal deaths occurring at gestational ages early in the reporting period (Technical Notes). Additionally, the small numbers of fetal deaths in some states by year can result in lack of reliability for state-specific fetal mortality rates. To try to address these issues, in addition to showing fetal mortality rates at 20 weeks or more by state for 2023, this report also presents fetal deaths and fetal mortality rates by state for fetal deaths at 24 weeks of gestation or more for the latest combined 3-year period (2021–2023).

### Cause of death

The National Center for Health Statistics codes the cause of fetal death reported by the certifier using the International Classification of Diseases, 10th Revision (12). In this report, the five most frequently reported causes of death shown, including unspecified cause, are drawn from 45 causes in the List of 124 Selected Causes of Fetal Death, as defined in Instruction manual, part 9 (13) and ranked according to the number of fetal deaths.

Data on the five causes of death are included for the 38 states and D.C. that reported cause of death based on the 2003 revision of the U.S. Standard Report of Fetal Death for the full year and met the reporting requirement of having less than 50% of records assigned to unspecified cause (P95). This reporting area includes 13,623 fetal deaths, representing 68.1% of all fetal deaths in 2023. These statistics based on a subnational area are not generalizable to the entire United States. In tables and figures, the five selected causes are shown in descending order according to the number of deaths assigned to each cause.

### Statistical significance

Statements in this report have been tested for statistical significance. A statement that a given mortality rate is higher or lower than another rate indicates that the rates are significantly different unless otherwise noted. For information on the methods used to test for statistical significance, as well as more detailed information on the collection, interpretation, and availability of fetal death data, see the 2023 User Guide (2).

## Results

### Trends in fetal mortality

- In 2023, 20,005 fetal deaths occurring at 20 weeks of gestation or more were reported in the United States, a decline of 1% from 2022 (20,202) (Table 1, Figure 1).
- The fetal mortality rate was 5.53 fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths in 2023, not significantly different from the 2022 rate of 5.48. With minor fluctuations, the total U.S. fetal mortality rate has declined 26% since 1990 (7.49).
- The early fetal mortality rate (20–27 weeks of gestation) increased 4% from 2022 (2.79) to 2023 (2.89), marking the first statistically significant annual increase in the rate since 2014. The rate had generally declined from 2014 (3.16) to 2022.
- The late fetal mortality rate (28 weeks of gestation or more) was 2.66 in 2023, not significantly different from the 2022 rate of 2.71. The rate fluctuated from 2014 (2.83) to 2023 for a total decline of 6%.

Figure 1

Fetal mortality rate: United States, 1990–2023

NOTE: Fetal mortality rate is the number of fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 1 is a line chart showing the fetal mortality rate in the United States for 1990 through 2023.

Table 1

Number of fetal deaths and births and fetal mortality rate for 1990–2023 and early and late fetal deaths and fetal mortality rate for 2014–2023: United States

Year | Fetal deaths | | | Live births | Fetal mortality rate^1^
Year | Total^2^ | 20–27 weeks^3^ | 28 weeks or more^3^ | Live births | Total^2^ | 20–27 weeks^3^ | 28 weeks or more^3^
2023 | 20,005 | 10,431 | 9,574 | 3,596,017 | 5.53 | 2.89 | 2.66
2022 | 20,202 | 10,246 | 9,956 | 3,667,758 | 5.48 | 2.79 | 2.71
2021 | 21,105 | 10,824 | 10,281 | 3,664,292 | 5.73 | 2.95 | 2.80
2020 | 20,854 | 10,764 | 10,090 | 3,613,647 | 5.74 | 2.97 | 2.78
2019 | 21,478 | 11,216 | 10,262 | 3,747,540 | 5.70 | 2.98 | 2.73
2018 | 22,459 | 11,844 | 10,615 | 3,791,712 | 5.89 | 3.11 | 2.79
2017 | 22,827 | 11,861 | 10,966 | 3,855,500 | 5.89 | 3.07 | 2.84
2016 | 23,880 | 12,486 | 11,394 | 3,945,875 | 6.02 | 3.15 | 2.88
2015 | 23,776 | 12,407 | 11,369 | 3,978,497 | 5.94 | 3.11 | 2.85
2014^4^ | 23,980 | 12,652 | 11,328 | 3,988,076 | 5.98 | 3.16 | 2.83
2013 | 23,595 | --- | --- | 3,932,181 | 5.96 | --- | ---
2012 | 24,073 | --- | --- | 3,952,841 | 6.05 | --- | ---
2011 | 24,289 | --- | --- | 3,953,590 | 6.11 | --- | ---
2010 | 24,258 | --- | --- | 3,999,386 | 6.03 | --- | ---
2009 | 24,872 | --- | --- | 4,130,665 | 5.99 | --- | ---
2008 | 26,335 | --- | --- | 4,247,726 | 6.16 | --- | ---
2007 | 26,593 | --- | --- | 4,316,233 | 6.12 | --- | ---
2006 | 25,972 | --- | --- | 4,265,593 | 6.05 | --- | ---
2005 | 25,894 | --- | --- | 4,138,573 | 6.22 | --- | ---
2004 | 26,001 | --- | --- | 4,112,055 | 6.28 | --- | ---
2003 | 26,004 | --- | --- | 4,090,007 | 6.32 | --- | ---
2002 | 25,943 | --- | --- | 4,021,825 | 6.41 | --- | ---
2001 | 26,373 | --- | --- | 4,026,036 | 6.51 | --- | ---
2000 | 27,003 | --- | --- | 4,058,882 | 6.61 | --- | ---
1995 | 27,294 | --- | --- | 3,899,589 | 6.95 | --- | ---
1990 | 31,386 | --- | --- | 4,158,445 | 7.49 | --- | ---

--- Data not available.

^1^Number of fetal deaths in specified group per 1,000 live births and fetal deaths.

^2^Fetal deaths with stated or presumed period of gestation of 20 weeks or more.

^3^Not stated gestational age proportionally distributed.

^4^Beginning with the 2014 data year, the obstetric estimate of gestation at delivery replaced the measure based on the date of last normal menses as the standard for measuring gestational age; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

### Race and Hispanic origin

- From 2022 to 2023, the fetal mortality rate increased 12% for Asian women (3.70 to 4.14). No significant changes in fetal mortality rates were observed for women of the remaining race and Hispanic-origin groups: American Indian and Alaska Native (7.22 to 6.87), Black (10.05 to 9.95), Native Hawaiian or Other Pacific Islander (10.36 to 10.18), White (4.48 to 4.55), and Hispanic (4.63 to 4.76) (Table 2, Figure 2).
- Among Hispanic-origin subgroups, no significant changes in fetal mortality rates were seen from 2022 to 2023: Central and South American (4.02 to 4.31), Cuban (3.85 to 4.81), Dominican (4.22 to 4.24), Mexican (4.68 to 4.63), Puerto Rican (4.64 to 4.89), and other and unknown Hispanic (5.81 to 6.44) women (Table 3).
- In 2023, fetal mortality rates continued to vary by race and Hispanic origin; rates were highest for Native Hawaiian or Other Pacific Islander (10.18) and Black (9.95) women, followed by American Indian and Alaska Native (6.87) women.
- The rate was lowest for Asian women (4.14), followed by White (4.55), and Hispanic (4.76) women.
- Among Hispanic-origin subgroups, in 2023, the rate was highest for other and unknown Hispanic (6.44) women. Rates for the other subgroups ranged from 4.24 for Dominican women to 4.89 for Puerto Rican women.

Figure 2

Fetal mortality rate, by race and Hispanic origin of mother: United States, 2022 and 2023

^1^Significant difference from all other groups (p < 0.05).

^2^Significantly higher than 2022 (p < 0.05).

^3^Significant difference from all groups except non-Hispanic Native Hawaiian or Other Pacific Islander (p < 0.05).

^4^Significant difference from all groups except non-Hispanic Black (p < 0.05).

^5^People of Hispanic origin may be of any race.

NOTE: Fetal mortality is the number of fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths in each specified group.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 2 Is a bar chart showing fetal mortality rates by race and Hispanic origin of mother for the United States for 2022 and 2023.

Table 2

Number of fetal deaths and mortality rate, by race and Hispanic origin of mother: United States, 2018–2023

Year | All races and origins^2^ | Non-Hispanic, single race^1^ | | | | | Hispanic^3^
Year | All races and origins^2^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian or Other Pacific Islander | White | Hispanic^3^
| Rate^4^
2023 | 5.53 | 6.87 | 4.14 | 9.95 | 10.18 | 4.55 | 4.76
2022 | 5.48 | 7.22 | 3.70 | 10.05 | 10.36 | 4.48 | 4.63
2021 | 5.73 | 7.48 | 3.94 | 9.89 | 9.87 | 4.85 | 4.82
2020 | 5.74 | 7.84 | 3.93 | 10.34 | 10.59 | 4.73 | 4.86
2019 | 5.70 | 7.47 | 4.02 | 10.41 | 10.03 | 4.71 | 4.79
2018 | 5.89 | 6.25 | 4.26 | 10.64 | 9.93 | 4.89 | 5.06
| Fetal deaths
2023 | 20,005 | 170 | 897 | 4,941 | 104 | 8,171 | 4,520
2022 | 20,202 | 187 | 813 | 5,194 | 106 | 8,280 | 4,359
2021 | 21,105 | 197 | 846 | 5,173 | 95 | 9,196 | 4,290
2020 | 20,854 | 212 | 864 | 5,536 | 103 | 8,753 | 4,231
2019 | 21,478 | 214 | 963 | 5,766 | 99 | 9,067 | 4,264
2018 | 22,459 | 183 | 1,029 | 5,938 | 95 | 9,621 | 4,510

^1^Race and Hispanic origin are reported separately on reports of fetal death; people of Hispanic origin may be of any race. In this table, non-Hispanic women are classified by race. Race categories are consistent with the 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the report of fetal death.

^2^Includes fetal deaths to race and Hispanic-origin groups not shown separately.

^3^Includes all people of Hispanic origin of any race; see Technical Notes.

^4^Number of fetal deaths in specified group per 1,000 live births and fetal deaths.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Table 3

Number of fetal deaths and mortality rate, by Hispanic origin of mother: United States, 2018–2023

Year | Total | Central and South American | Cuban | Dominican | Mexican | Puerto Rican | Other and Unknown Hispanic
| Rate^1^
2023 | 4.76 | 4.31 | 4.81 | 4.24 | 4.63 | 4.89 | 6.44
2022 | 4.63 | 4.02 | 3.85 | 4.22 | 4.68 | 4.64 | 5.81
2021 | 4.82 | --- | 4.81 | 4.39 | 4.77 | 5.11 | ---
2020 | 4.86 | --- | 5.23 | 4.41 | 4.79 | 4.98 | ---
2019 | 4.79 | --- | 4.71 | 4.75 | 4.86 | 5.17 | ---
2018 | 5.06 | --- | 4.16 | 5.09 | 5.19 | 5.07 | ---
| Fetal deaths
2023 | 4,520 | 902 | 145 | 143 | 2,365 | 325 | 640
2022 | 4,359 | 779 | 102 | 142 | 2,400 | 323 | 613
2021 | 4,290 | --- | 118 | 147 | 2,325 | 363 | ---
2020 | 4,231 | --- | 122 | 140 | 2,312 | 349 | ---
2019 | 4,264 | --- | 112 | 155 | 2,427 | 369 | ---
2018 | 4,510 | --- | 98 | 164 | 2,587 | 365 | ---

--- Data not available.

^1^Number of fetal deaths in specified group per 1,000 live births and fetal deaths.

NOTE: In this table, Hispanic women are classified only by place of origin; non-Hispanic women are not shown.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

### Maternal age

- Fetal mortality rates varied by maternal age (Table 4, Figure 3). In 2023, rates were highest for females younger than 15 (12.86) and ages 40–44 (8.36) and 45 and older (13.25) and lowest for women ages 25–29 (5.07) and 30–34 (5.15).
- The fetal mortality rate for teenagers ages 15–17 (7.89) was more than 50% higher, and the rate for teenagers ages 18–19 (6.58) was 28%–30% higher, than the rates for women ages 25–29 (5.07) and 30–34 (5.15).
- Age-specific rates for Black females were higher than those for White and Hispanic females ages 15–44, and higher than those for Asian women ages 20–44.

Figure 3

Fetal mortality rate, by age of mother: United States, 2023

^1^Significant difference from all other groups except 40–44 and 45 and older (p < 0.05).

^2^Significant difference from all other groups (p < 0.05).

^3^Significant difference from all age groups except 30–34 (p < 0.05).

^4^Significant difference from all age groups except 25–29 (p < 0.05).

^5^Significant difference from all age groups except younger than 15 (p < 0.05).

NOTE: Fetal mortality is the number of fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths in each specified group.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 3 is a bar chart showing fetal mortality rates by age of mother for the United States for 2023.

Table 4

Number and rate of total, early, and late fetal deaths, by age and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin and age of mother | Fetal deaths | | | Fetal mortality rate^1^
Race and Hispanic origin and age of mother | Total | 20–27 weeks^2^ | 28 weeks or more^2^ | Total | 20–27 weeks^2^ | 28 weeks or more^2^
All races and origins^3^ | 20,005 | 10,431 | 9,574 | 5.53 | 2.89 | 2.66
Younger than 15 | 23 | 16 | * | 12.86 | 8.98 | *
15–19 | 981 | 531 | 450 | 6.91 | 3.75 | 3.18
15–17 | 284 | 155 | 129 | 7.89 | 4.32 | 3.60
18–19 | 697 | 376 | 321 | 6.58 | 3.56 | 3.04
20–24 | 3,420 | 1,781 | 1,639 | 5.51 | 2.88 | 2.65
25–29 | 5,031 | 2,540 | 2,491 | 5.07 | 2.57 | 2.52
30–34 | 5,689 | 2,935 | 2,754 | 5.15 | 2.67 | 2.50
35–39 | 3,567 | 1,936 | 1,631 | 5.86 | 3.19 | 2.69
40–44 | 1,150 | 608 | 542 | 8.36 | 4.44 | 3.96
45 and older | 144 | 84 | 60 | 13.25 | 7.77 | 5.57
Non-Hispanic, single race^4^:
Asian | 897 | 499 | 398 | 4.14 | 2.31 | 1.84
Younger than 15 | * | * | * | * | * | *
15–19 | 15 | * | * | 15.96 | * | *
15–17 | * | * | * | * | * | *
18–19 | 14 | * | * | 18.69 | * | *
20–24 | 45 | 23 | 22 | 4.75 | 2.44 | 2.33
25–29 | 171 | 89 | 82 | 4.17 | 2.17 | 2.00
30–34 | 340 | 176 | 164 | 3.83 | 1.98 | 1.85
35–39 | 246 | 152 | 94 | 4.03 | 2.49 | 1.54
40–44 | 70 | 43 | 27 | 4.99 | 3.07 | 1.93
45 and older | 10 | * | * | * | * | *
Black | 4,941 | 2,716 | 2,225 | 9.95 | 5.50 | 4.51
Younger than 15 | * | * | * | * | * | *
15–19 | 322 | 191 | 131 | 11.21 | 6.68 | 4.59
15–17 | 109 | 65 | 44 | 13.42 | 8.05 | 5.46
18–19 | 213 | 127 | 86 | 10.33 | 6.19 | 4.20
20–24 | 990 | 536 | 454 | 9.51 | 5.17 | 4.39
25–29 | 1,255 | 661 | 594 | 9.44 | 4.99 | 4.49
30–34 | 1,267 | 717 | 550 | 9.54 | 5.42 | 4.17
35–39 | 820 | 454 | 366 | 10.89 | 6.06 | 4.89
40–44 | 244 | 132 | 112 | 12.10 | 6.58 | 5.59
45 and older | 37 | 21 | 16 | 19.15 | 10.96 | 8.37
White | 8,171 | 4,141 | 4,030 | 4.55 | 2.31 | 2.25
Younger than 15 | * | * | * | * | * | *
15–19 | 277 | 144 | 133 | 6.13 | 3.20 | 2.95
15–17 | 63 | 27 | 36 | 6.78 | 2.92 | 3.89
18–19 | 214 | 117 | 97 | 5.96 | 3.27 | 2.71
20–24 | 1,236 | 626 | 610 | 4.66 | 2.37 | 2.31
25–29 | 2,089 | 1,028 | 1,061 | 4.15 | 2.05 | 2.11
30–34 | 2,527 | 1,264 | 1,263 | 4.22 | 2.12 | 2.12
35–39 | 1,528 | 801 | 727 | 4.84 | 2.54 | 2.31
40–44 | 456 | 245 | 211 | 7.23 | 3.90 | 3.36
45 and older | 54 | 31 | 23 | 11.70 | 6.75 | 5.02
Hispanic^5^ | 4,520 | 2,299 | 2,221 | 4.76 | 2.43 | 2.34
Younger than 15 | 10 | * | * | * | * | *
15–19 | 288 | 140 | 148 | 4.95 | 2.41 | 2.55
15–17 | 84 | 42 | 42 | 5.26 | 2.64 | 2.64
18–19 | 204 | 98 | 106 | 4.83 | 2.33 | 2.52
20–24 | 905 | 471 | 434 | 4.34 | 2.26 | 2.09
25–29 | 1,148 | 564 | 584 | 4.23 | 2.08 | 2.16
30–34 | 1,133 | 574 | 559 | 4.69 | 2.38 | 2.32
35–39 | 698 | 376 | 322 | 5.28 | 2.85 | 2.44
40–44 | 306 | 150 | 156 | 8.91 | 4.39 | 4.56
45 and older | 32 | 17 | 15 | 13.65 | 7.30 | 6.45

* Estimate does not meet National Center for Health Statistics standards of reliability.

^1^Number of fetal deaths in specified group per 1,000 live births and fetal deaths.

^2^Fetal deaths with gestational age not stated were proportionally distributed; see Technical Notes in this report.

^3^Includes fetal deaths to race and Hispanic-origin groups not shown separately.

^4^Race and Hispanic origin are reported separately on reports of fetal death; people of Hispanic origin may be of any race. In this table, non-Hispanic women are classified by race. Race categories are consistent with the 1997 Office of Management and Budget standards; see Technical Notes. Single race is defined as only one race reported on the report of fetal death.

^5^Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

### Tobacco use during pregnancy

- The fetal mortality rate for women who smoked cigarettes during pregnancy (9.92) was two times higher than that for women who did not smoke during pregnancy (4.91) (Table 5).
- The pattern was similar for the three largest race and Hispanic-origin groups. The fetal mortality rate for women who smoked during pregnancy compared with those who did not was two or more times higher for Black (18.59 and 8.99, respectively), White (8.19 and 4.03), and Hispanic (9.95 and 4.38) women. See Table 5 for fetal mortality rates by tobacco use during pregnancy by age.

Table 5

Fetal mortality rate, by tobacco use during pregnancy, age, and race and Hispanic origin of mother: 49 states and the District of Columbia, 2023

Race and Hispanic origin of mother and tobacco use during pregnancy | Fetal deaths | All ages | Younger than 20 | 20–24 | 25–29 | 30–34 | 35–39 | 40–54 | Not stated
All races and origins^1^ | Number | Fetal mortality rate^2^ | | | | | | | Number
Total | 19,915 | 5.53 | 6.97 | 5.51 | 5.07 | 5.16 | 5.86 | 8.73 | 1,769
Yes | 1,078 | 9.92 | 8.20 | 8.35 | 8.66 | 10.49 | 11.90 | 16.10 | …
No | 17,068 | 4.91 | 6.23 | 4.92 | 4.53 | 4.56 | 5.14 | 7.78 | …
Non-Hispanic, single race^3^
Asian:
Total | 893 | 4.19 | 15.22 | 4.88 | 4.25 | 3.87 | 4.06 | 5.32 | 65
Yes | * | * | * | * | * | * | * | * | …
No | 822 | 3.87 | * | 4.26 | 4.04 | 3.57 | 3.71 | 5.02 | …
Black:
Total | 4,940 | 9.96 | 11.22 | 9.52 | 9.45 | 9.55 | 10.88 | 12.72 | 372
Yes | 253 | 18.59 | * | 19.98 | 19.05 | 15.60 | 19.70 | 28.70 | …
No | 4,315 | 8.99 | 10.27 | 8.77 | 8.48 | 8.56 | 9.74 | 11.35 | …
White:
Total | 8,162 | 4.55 | 6.17 | 4.67 | 4.15 | 4.23 | 4.84 | 7.56 | 635
Yes | 652 | 8.19 | 7.92 | 6.84 | 6.70 | 8.88 | 10.07 | 14.47 | …
No | 6,875 | 4.03 | 5.38 | 4.15 | 3.72 | 3.71 | 4.27 | 6.69 | …
Hispanic^4^
Total | 4,509 | 4.76 | 5.04 | 4.34 | 4.23 | 4.70 | 5.27 | 9.21 | 333
Yes | 73 | 9.95 | * | 10.48 | 9.77 | 11.16 | * | * | …
No | 4,103 | 4.38 | 4.54 | 3.91 | 3.92 | 4.36 | 4.85 | 8.53 | …

… Category not applicable.

* Estimate does not meet National Center for Health Statistics standards of reliability.

^1^Includes fetal deaths to race and Hispanic-origin groups not shown separately.

^2^Number of fetal deaths in specified group per 1,000 live births and fetal deaths.

^3^Race and Hispanic origin are reported separately on the report of fetal death; people of Hispanic origin may be of any race. In this table, non-Hispanic women are classified by race. Race categories are consistent with the 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the report of fetal death.

^4^Includes all people of Hispanic origin of any race; see Technical Notes.

NOTE: Findings exclude data for Hawaii; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Table 6

Number of fetal deaths and mortality rate, by birthweight, gestational age, and race and Hispanic origin of mother: United States, 2023

Race and Hispanic origin of mother and birthweight (grams) | Gestational age (weeks) | | | | | | | | | | | Fetal mortality rate^1^
Race and Hispanic origin of mother and birthweight (grams) | Total | 20–23 | 24–27 | 28–31 | 32–33 | 34–36 | 37–38 | 39–40 | 41 | 42 or more | Not stated | Fetal mortality rate^1^
All races and origins^2^ | 20,005 | 7,206 | 3,159 | 2,618 | 1,386 | 2,407 | 1,766 | 1,145 | 138 | 54 | 126 | 5.53
Less than 500 | 6,733 | 5,354 | 1,032 | 216 | 42 | 27 | 32 | * | * | * | 19 | 584.82
500–749 | 2,094 | 786 | 957 | 283 | 34 | 17 | * | * | * | * | 11 | 201.21
750–999 | 1,290 | 161 | 598 | 427 | 55 | 34 | * | * | * | * | * | 119.41
1,000–1,249 | 983 | 41 | 205 | 548 | 116 | 55 | * | * | * | * | * | 79.46
1,250–1,499 | 883 | 22 | 66 | 448 | 188 | 126 | 26 | * | * | * | * | 56.17
1,500–1,999 | 1,613 | 19 | 42 | 444 | 503 | 473 | 99 | 24 | * | * | * | 26.35
2,000–2,499 | 1,489 | * | 13 | 83 | 280 | 766 | 251 | 78 | * | * | 14 | 7.40
2,500–2,999 | 1,416 | * | * | 21 | 60 | 506 | 533 | 254 | 18 | * | 12 | 1.99
3,000–3,499 | 1,123 | * | * | * | 29 | 185 | 445 | 383 | 52 | 11 | * | 0.80
3,500–3,999 | 539 | * | * | * | * | 79 | 178 | 221 | 32 | 14 | * | 0.59
4,000 or more | 316 | * | * | * | * | 40 | 107 | 124 | 20 | 14 | * | 1.24
Not stated | 1,526 | 823 | 242 | 134 | 66 | 99 | 75 | 37 | * | * | 37 | …
Fetal mortality rate^1^ | 5.53 | 528.14 | 169.47 | 73.19 | 31.22 | 8.69 | 1.64 | 0.58 | 0.84 | 5.77 | … | …
Non-Hispanic, single race^3^:
Asian | 897 | 356 | 140 | 99 | 53 | 98 | 75 | 63 | * | * | * | 4.14
Less than 500 | 317 | 265 | 37 | * | * | * | * | * | * | * | * | 632.73
500–749 | 107 | 39 | 48 | 15 | * | * | * | * | * | * | * | 219.71
750–999 | 51 | * | 31 | 10 | * | * | * | * | * | * | * | 90.27
1,000–1,249 | 46 | * | * | 24 | * | * | * | * | * | * | * | 70.12
1,250–1,499 | 32 | * | * | 19 | * | * | * | * | * | * | * | 39.51
1,500–1,999 | 66 | * | * | 19 | 19 | 24 | * | * | * | * | * | 17.65
2,000–2,499 | 66 | * | * | * | 11 | 36 | 13 | * | * | * | * | 4.62
2,500–2,999 | 57 | * | * | * | * | 12 | 22 | 17 | * | * | * | 1.02
3,000–3,499 | 56 | * | * | * | * | * | 19 | 29 | * | * | * | 0.62
3,500–3,999 | 19 | * | * | * | * | * | * | * | * | * | * | 0.46
4,000 or more | * | * | * | * | * | * | * | * | * | * | * | *
Not stated | 73 | 43 | 13 | * | * | * | * | * | * | * | * | …
Fetal mortality rate^1^ | 4.14 | 581.70 | 154.87 | 55.90 | 23.68 | 6.65 | 1.09 | 0.52 | * | * | … | …
Black | 4,941 | 1,828 | 867 | 728 | 355 | 564 | 348 | 184 | 19 | 10 | 38 | 9.95
Less than 500 | 1,829 | 1,423 | 305 | 70 | 12 | 10 | * | * | * | * | * | 525.12
500–749 | 544 | 183 | 280 | 67 | * | * | * | * | * | * | * | 167.38
750–999 | 331 | 32 | 151 | 120 | 15 | 12 | * | * | * | * | * | 105.92
1,000–1,249 | 292 | 11 | 53 | 173 | 29 | 20 | * | * | * | * | * | 86.65
1,250–1,499 | 269 | * | 18 | 145 | 57 | 37 | * | * | * | * | * | 65.85
1,500–1,999 | 404 | * | 10 | 93 | 140 | 122 | 25 | * | * | * | * | 27.91
2,000–2,499 | 356 | * | * | 18 | 67 | 195 | 58 | 11 | * | * | * | 7.93
2,500–2,999 | 278 | * | * | * | 10 | 93 | 119 | 45 | * | * | * | 2.13
3,000–3,499 | 172 | * | * | * | * | 30 | 71 | 53 | 10 | * | * | 0.94
3,500–3,999 | 85 | * | * | * | * | 16 | 28 | 33 | * | * | * | 0.99
4,000 or more | 64 | * | * | * | * | * | 27 | 25 | * | * | * | 3.30
Not stated | 317 | 172 | 49 | 36 | 16 | 20 | * | * | * | * | * | …
Fetal mortality rate^1^ | 9.95 | 459.76 | 161.63 | 84.50 | 38.25 | 11.59 | 2.11 | 0.78 | 1.13 | * | … | …
White | 8,171 | 2,844 | 1,278 | 1,012 | 543 | 1,016 | 800 | 535 | 74 | 31 | 38 | 4.55
Less than 500 | 2,643 | 2,100 | 424 | 70 | 13 | * | 16 | * | * | * | * | 647.95
500–749 | 815 | 291 | 379 | 119 | 15 | * | * | * | * | * | * | 230.03
750–999 | 514 | 61 | 243 | 170 | 20 | 12 | * | * | * | * | * | 133.23
1,000–1,249 | 360 | 15 | 78 | 205 | 41 | 14 | * | * | * | * | * | 74.80
1,250–1,499 | 311 | * | 23 | 150 | 71 | 45 | 12 | * | * | * | * | 49.65
1,500–1,999 | 627 | * | 17 | 187 | 198 | 168 | 41 | * | * | * | * | 24.84
2,000–2,499 | 643 | * | * | 43 | 120 | 324 | 109 | 35 | * | * | * | 7.67
2,500–2,999 | 653 | * | * | * | 25 | 260 | 240 | 105 | * | * | * | 2.17
3,000–3,499 | 547 | * | * | * | 14 | 83 | 223 | 183 | 29 | * | * | 0.80
3,500–3,999 | 260 | * | * | * | * | 34 | 82 | 112 | 15 | * | * | 0.50
4,000 or more | 139 | * | * | * | * | 13 | 34 | 65 | 12 | * | * | 0.89
Not stated | 659 | 363 | 107 | 53 | 19 | 51 | 31 | 18 | * | * | 11 | …
Fetal mortality rate^1^ | 4.55 | 598.61 | 187.28 | 69.63 | 27.19 | 7.88 | 1.58 | 0.53 | 0.80 | 5.10 | … | …
Hispanic^4^ | 4,520 | 1,642 | 647 | 584 | 324 | 559 | 429 | 277 | 30 | * | 20 | 4.76
Less than 500 | 1,495 | 1,218 | 195 | 54 | 10 | * | 10 | * | * | * | * | 551.46
500–749 | 471 | 207 | 187 | 61 | * | * | * | * | * | * | * | 182.63
750–999 | 299 | 43 | 138 | 93 | 13 | * | * | * | * | * | * | 111.69
1,000–1,249 | 219 | * | 50 | 111 | 28 | 16 | * | * | * | * | * | 75.80
1,250–1,499 | 218 | * | 18 | 105 | 46 | 34 | * | * | * | * | * | 57.70
1,500–1,999 | 395 | * | 10 | 110 | 114 | 119 | 26 | * | * | * | * | 26.82
2,000–2 499 | 322 | * | * | 15 | 59 | 162 | 60 | 18 | * | * | * | 6.58
2 500–2,999 | 331 | * | * | * | 19 | 105 | 123 | 65 | * | * | * | 1.73
3,000–3,499 | 268 | * | * | * | * | 46 | 105 | 95 | * | * | * | 0.69
3,500–3,999 | 142 | * | * | * | * | 23 | 46 | 56 | 12 | * | * | 0.61
4,000 or more | 84 | * | * | * | * | 17 | 33 | 25 | * | * | * | 1.42
Not stated | 276 | 150 | 42 | 25 | 13 | 17 | 17 | * | * | * | * | …
Fetal mortality rate^1^ | 4.76 | 484.22 | 141.79 | 65.34 | 30.17 | 7.81 | 1.49 | 0.53 | 0.76 | * | … | …

* Estimate does not meet National Center for Health Statistics standards of reliability.

… Category not applicable.

^1^Number of fetal deaths in specified group per 1,000 live births and fetal deaths.

^2^Includes fetal deaths to race and Hispanic-origin groups not shown separately.

^3^Race and Hispanic origin are reported separately on the report of fetal death; people of Hispanic origin may be of any race. In this table, non-Hispanic women are classified by race. Race categories are consistent with the 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the report of fetal death.

^4^Includes all people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

### Plurality

- The fetal mortality rate for twins (12.64) was more than twice that for singletons (5.29) (Table A). The rate for triplet or higher-order deliveries (22.84) was more than four times that for singletons.
- The pattern was similar for the five largest race and Hispanic-origin groups. For example, the fetal mortality rate for twins compared with singletons was more than twice as high for American Indian and Alaska Native (20.53 and 6.49, respectively), Asian (9.53 and 3.99), White (10.81 and 4.33), and Hispanic (12.35 and 4.56) women, and nearly twice as high for Black women (16.86 and 9.62).

Table A

Fetal mortality rate, by selected characteristics and race and Hispanic origin of mother: United States, 2023

Characteristic | Total^1^ | Non-Hispanic, single race^2^ | | | | | Hispanic^3^
Characteristic | Total^1^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian or Other Pacific Islander | White | Hispanic^3^
| Fetal mortality rate^4^
Total | 5.53 | 6.87 | 4.14 | 9.95 | 10.18 | 4.55 | 4.76
Plurality
Single | 5.29 | 6.49 | 3.99 | 9.62 | 9.96 | 4.33 | 4.56
Twin | 12.64 | 20.53 | 9.53 | 16.86 | * | 10.81 | 12.35
Triplet or higher order | 22.84 | * | * | 34.30 | * | 20.88 | *
Sex of fetus
Male | 5.61 | 7.78 | 3.99 | 10.49 | 10.89 | 4.54 | 4.79
Female | 5.45 | 5.93 | 4.30 | 9.40 | 9.46 | 4.57 | 4.73
Male–female ratio | 1.03 | 1.31 | 0.93 | 1.12 | 1.15 | 0.99 | 1.01
| Fetal deaths
Total | 20,005 | 170 | 897 | 4,941 | 104 | 8,171 | 4,520
Plurality
Single | 18,530 | 156 | 843 | 4,573 | 99 | 7,523 | 4,222
Twin | 1,413 | 14 | 51 | 349 | * | 619 | 287
Triplet or higher order | 62 | * | * | 19 | * | 29 | 11
Sex of fetus
Male | 10,377 | 98 | 447 | 2,649 | 56 | 4,175 | 2,322
Female | 9,628 | 72 | 450 | 2,292 | 48 | 3,996 | 2,198
Male–female ratio | … | … | … | … | … | … | …
| Live births
Total | 3,596,017 | 24,571 | 215,738 | 491,494 | 10,115 | 1,787,051 | 945,200
Plurality
Single | 3,482,971 | 23,899 | 210,328 | 470,612 | 9,842 | 1,729,043 | 921,711
Twin | 110,393 | 668 | 5,300 | 20,347 | 270 | 56,648 | 22,954
Triplet or higher order | 2,653 | * | 110 | 535 | * | 1,360 | 535
Sex of fetus
Male | 1,839,794 | 12,505 | 111,542 | 249,931 | 5,087 | 916,170 | 482,254
Female | 1,756,223 | 12,066 | 104,196 | 241,563 | 5,028 | 870,881 | 462,946
Male–female ratio | … | … | … | … | … | … | …

* Estimate does not meet National Center for Health Statistics standards of reliability.

… Category not applicable.

^1^Includes fetal deaths to race and Hispanic-origin groups not shown separately.

^2^Race and Hispanic origin are reported separately on the report of fetal death; people of Hispanic origin may be of any race. In this table, non-Hispanic women are classified by race. Race categories are consistent with the 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the report of fetal death.

^3^Includes all people of Hispanic origin of any race; see Technical Notes.

^4^Number of fetal deaths in specified group per 1,000 live births and fetal deaths.

SOURCE: National Center for Vital Statistics, National Vital Statistics System.

### Sex of fetus

- In 2023, the fetal mortality rate for male fetuses was 5.61, 3% higher than the rate for female fetuses (5.45) (Table A).
- The fetal mortality rate for male fetuses compared with female fetuses was 12% higher for Black women (10.49 and 9.40, respectively). No significant difference was seen for American Indian and Alaska Native (7.78 and 5.93), Asian (3.99 and 4.30), Native Hawaiian or Other Pacific Islander (10.89 and 9.46), White (4.54 and 4.57), and Hispanic (4.79 and 4.73) women.

### Period of gestation

- In 2023, just over one-half of all fetal deaths at 20 weeks of gestation or more (52.1%) occurred at 20–27 weeks (early fetal deaths), and 47.9% occurred at 28 weeks of gestation or more (late fetal deaths) (Table 6).
- The fetal mortality rate was highest at 20–23 weeks of gestation (528.14), declined to a low of 0.58 at 39–40 weeks, and then increased to 5.77 at 42 weeks of gestation or more.

### Birthweight

- In 2023, more than one-third of fetal deaths at 20 weeks of gestation or more (36.4%) weighed less than 500 grams (1 lb. 1 oz.) at delivery, and nearly one-half (47.8%) weighed less than 750 grams (1 lb. 12 oz.) (Table 6).
- The fetal mortality rate was highest for fetuses weighing less than 500 grams (584.82) and decreased with increasing birthweight to a low of 0.59 for fetuses weighing 3,500–3,999 grams. Fetal mortality rates then increased slightly for fetuses weighing 4,000 grams or more (1.24).

### Fetal mortality rates by state

- For combined years 2021–2023, the U.S. fetal mortality rate for fetal deaths at 24 weeks or more was 3.59 per 1,000 live births and fetal deaths (Table B).
- For combined years 2021–2023, fetal mortality rates were highest (above 5.00) in Mississippi (6.05) and Alabama (5.07), and lowest (below 3.00) in Texas (2.78), Vermont (2.78), Massachusetts (2.86), Montana (2.86), Maine (2.90), Connecticut (2.91), New Mexico (2.92), and Iowa (2.97).
- See Table 7 for fetal deaths at 20 weeks of gestation or more by state and territory for 2023.

Table 7

Number of fetal deaths at 20 weeks of gestation or more and fetal mortality rate: United States and each state and territory, 2023

Area | Fetal deaths^1^ | Fetal mortality rate^2^ | Area | Fetal deaths^1^ | Fetal mortality rate^2^
Total | 20,005 | 5.53 | New Jersey | 562 | 5.53
Alabama | 436 | 7.48 | New Mexico | 94 | 4.47
Alaska | 42 | 4.64 | New York | 1,137 | 5.55
Arizona | 494 | 6.29 | North Carolina | 697 | 5.77
Arkansas | 248 | 6.98 | North Dakota | 42 | 4.33
California | 1,993 | 4.96 | Ohio | 775 | 6.07
Colorado | 378 | 6.11 | Oklahoma | 275 | 5.71
Connecticut | 171 | 4.92 | Oregon | 179 | 4.65
Delaware | 62 | 5.91 | Pennsylvania | 593 | 4.65
District of Columbia | 55 | 6.92 | Rhode Island | 49 | 4.97
Florida | 1,509 | 6.77 | South Carolina | 310 | 5.34
Georgia | 959 | 7.61 | South Dakota | 84 | 7.44
Hawaii | 90 | 6.04 | Tennessee | 471 | 5.64
Idaho | 123 | 5.46 | Texas | 1,615 | 4.15
Illinois | 740 | 5.89 | Utah | 296 | 6.53
Indiana | 496 | 6.24 | Vermont | 19 | 3.74
Iowa | 159 | 4.39 | Virginia | 495 | 5.31
Kansas | 184 | 5.37 | Washington | 432 | 5.31
Kentucky | 277 | 5.30 | West Virginia | 62 | 3.72
Louisiana | 296 | 5.36 | Wisconsin | 314 | 5.23
Maine | 41 | 3.51 | Wyoming | 33 | 5.48
Maryland | 430 | 6.51 | American Samoa | --- | ---
Massachusetts | 261 | 3.88 | Guam | 35 | 14.66
Michigan | 532 | 5.34 | Northern Marianas | --- | ---
Minnesota | 319 | 5.14 | Puerto Rico | 221 | 11.74
Mississippi | 343 | 9.86 | U.S. Virgin Islands | --- | ---
Missouri | 372 | 5.51
Montana | 49 | 4.40
Nebraska | 123 | 5.08
Nevada | 245 | 7.65
New Hampshire | 44 | 3.67

--- Data not available.

^1^Fetal deaths with stated or presumed period of gestation of 20 weeks or more.

^2^Number of fetal deaths per 1,000 live births and fetal deaths.

NOTES: American Samoa did not report data for 2023. Data for the Northern Marianas and the U.S. Virgin Islands were excluded due to small numbers.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Table B

Number of fetal deaths at 24 weeks of gestation or more and fetal mortality rate, by state and territory: United States, 2021–2023

Area | Fetal deaths | Fetal mortality rate^1^
Total | 39,400 | 3.59
Alabama | 887 | 5.07
Alaska | 104 | 3.73
Arizona | 986 | 4.19
Arkansas | 526 | 4.91
California | 4,169 | 3.35
Colorado | 615 | 3.28
Connecticut | 308 | 2.91
Delaware | 115 | 3.61
District of Columbia | 119 | 4.81
Florida | 2,942 | 4.42
Georgia | 1,801 | 4.78
Hawaii | 184 | 3.99
Idaho | 212 | 3.14
Illinois | 1,295 | 3.35
Indiana | 828 | 3.46
Iowa | 326 | 2.97
Kansas | 401 | 3.87
Kentucky | 600 | 3.82
Louisiana | 611 | 3.61
Maine | 104 | 2.90
Maryland | 769 | 3.78
Massachusetts | 587 | 2.86
Michigan | 1,141 | 3.71
Minnesota | 661 | 3.46
Mississippi | 635 | 6.05
Missouri | 763 | 3.70
Montana | 96 | 2.86
Nebraska | 224 | 3.06
Nevada | 449 | 4.53
New Hampshire | 125 | 3.40
New Jersey | 954 | 3.11
New Mexico | 187 | 2.92
New York | 2,127 | 3.41
North Carolina | 1,366 | 3.76
North Dakota | 92 | 3.13
Ohio | 1,463 | 3.79
Oklahoma | 558 | 3.84
Oregon | 403 | 3.38
Pennsylvania | 1,271 | 3.25
Rhode Island | 102 | 3.33
South Carolina | 727 | 4.19
South Dakota | 131 | 3.86
Tennessee | 1,058 | 4.27
Texas | 3,214 | 2.78
Utah | 513 | 3.72
Vermont | 44 | 2.78
Virginia | 941 | 3.30
Washington | 809 | 3.25
West Virginia | 180 | 3.54
Wisconsin | 605 | 3.32
Wyoming | 79 | 4.30
American Samoa | --- | ---
Guam | 80 | 10.56
Northern Marianas | --- | ---
Puerto Rico | 359 | 6.26
U.S. Virgin Islands | --- | ---

--- Data not available.

^1^Number of fetal deaths in specified group per 1,000 live births and fetal deaths.

NOTES: Fetal deaths with not-stated period of gestation are proportionally distributed to less than 24 weeks and 24 weeks or more; see Technical Notes in this report. Numbers may not add to totals due to rounding.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

### Selected causes of fetal death

- The five most common selected causes of fetal death accounted for 89.9% of fetal deaths in the 38-state and D.C. reporting area (Table 8, Figure 4). By order of frequency, these were: 1) Fetal death of unspecified cause (unspecified cause); 2) Fetus affected by complications of placenta, cord and membranes (placental, cord and membrane complications); 3) Fetus affected by maternal complications of pregnancy (maternal complications); 4) Congenital malformations, deformations and chromosomal abnormalities (congenital malformations); and 5) Fetus affected by maternal conditions that may be unrelated to present pregnancy (maternal conditions unrelated to pregnancy).
- The five most common selected causes of fetal death were the same for the six largest race and Hispanic-origin groups. Unspecified cause was the top category for all groups, while the ranking of the other causes differed.
- Placental, cord and membrane complications was the second most common cause of fetal death for all race and Hispanic-origin groups except for Native Hawaiian or Other Pacific Islander women, for whom maternal complications was the second most common cause.
- Maternal complications, congenital malformations, and maternal conditions unrelated to pregnancy comprised the third through fifth most common causes for all groups except for Native Hawaiian or Other Pacific Islander women, for whom placental, cord and membrane complications replaced maternal complications.

Figure 4

Percent distribution of fetal deaths, by selected causes of death and race and Hispanic origin of mother: 38 states and District of Columbia, 2023

* Estimate does not meet National Center for Health Statistics standards of reliability.

^1^People of Hispanic origin may be of any race.

NOTES: Codes in parentheses are cause-of-death codes as classified by the International Statistical Classification of Diseases and Related Health Problems, 10th Revision. Excludes data for jurisdictions (Arizona, Georgia, Hawaii, Michigan, Mississippi, Nevada, New York [including New York City], North Dakota, Vermont, Virginia, and Wyoming) for which the cause of death was unspecified (P95) for 50% or more of records. Also excludes data for California, which did not report cause of death based on the 2003 revision of the U.S. Standard Report of Fetal Death for the full year. Figures may not add to 100.0 because of rounding.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

Figure 4 Is a stacked bar chart showing the percent distribution of fetal deaths by selected causes of death and race and Hispanic origin of mother for 38 states and the District of Columbia for 2023.

Table 8

Number of fetal deaths and percentage of total deaths for the five selected causes, by race and Hispanic origin of mother: 38 states and the District of Columbia, 2023

Rank | Cause and race and Hispanic origin of mother | Fetal deaths | Percent
| All races and origins^1^
… | All causes | 13,623 | 100.0
1 | Fetal death of unspecified cause(P95) | 4,266 | 31.3
2 | Fetus affected by complications of placenta, cord and membranes(P02) | 3,486 | 25.6
3 | Fetus affected by maternal complications of pregnancy(P01) | 1,615 | 11.9
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 1,463 | 10.7
5 | Fetus affected by maternal conditions that may be unrelated to present pregnancy(P00) | 1,420 | 10.4
… | All other causes | 1,373 | 10.1
| Non-Hispanic, single race^2^
| American Indian and Alaska Native:
… | All causes | 120 | 100.0
1 | Fetal death of unspecified cause(P95) | 33 | 27.5
2 | Fetus affected by complications of placenta, cord and membranes(P02) | 29 | 24.2
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 18 | 15.0
4 | Fetus affected by maternal conditions that may be unrelated to present pregnancy(P00) | 13 | 10.8
5 | Fetus affected by maternal complications of pregnancy(P01) | * | *
… | All other causes | 18 | 15.0
| Asian:
… | All causes | 498 | 100.0
1 | Fetal death of unspecified cause(P95) | 142 | 28.5
2 | Fetus affected by complications of placenta, cord and membranes(P02) | 125 | 25.1
3 | Fetus affected by maternal complications of pregnancy(P01) | 70 | 14.1
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 64 | 12.9
5 | Fetus affected by maternal conditions that may be unrelated to present pregnancy(P00) | 40 | 8.0
… | All other causes | 57 | 11.4
| Black:
… | All causes | 3,340 | 100.0
1 | Fetal death of unspecified cause(P95) | 972 | 29.1
2 | Fetus affected by complications of placenta, cord and membranes(P02) | 840 | 25.1
3 | Fetus affected by maternal complications of pregnancy(P01) | 498 | 14.9
3 | Fetus affected by maternal conditions that may be unrelated to present pregnancy(P00) | 498 | 14.9
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 240 | 7.2
… | All other causes | 292 | 8.7
| Native Hawaiian or Other Pacific Islander:
… | All causes | 63 | 100.0
1 | Fetal death of unspecified cause(P95) | 17 | 27.0
2 | Fetus affected by maternal complications of pregnancy(P01) | 15 | 23.8
3 | Fetus affected by complications of placenta, cord and membranes(P02) | 11 | 17.5
4 | Fetus affected by maternal conditions that may be unrelated to present pregnancy(P00) | * | *
5 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | * | *
… | All other causes | * | *
| White:
… | All causes | 6,187 | 100.0
1 | Fetal death of unspecified cause(P95) | 2,058 | 33.3
2 | Fetus affected by complications of placenta, cord and membranes(P02) | 1,634 | 26.4
3 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 754 | 12.2
4 | Fetus affected by maternal complications of pregnancy(P01) | 610 | 9.9
5 | Fetus affected by maternal conditions that may be unrelated to present pregnancy(P00) | 540 | 8.7
… | All other causes | 591 | 9.6
| Hispanic^3^
… | All causes | 2,788 | 100.0
1 | Fetal death of unspecified cause(P95) | 837 | 30.0
2 | Fetus affected by complications of placenta, cord and membranes(P02) | 703 | 25.2
3 | Fetus affected by maternal complications of pregnancy(P01) | 336 | 12.1
4 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 331 | 11.9
5 | Fetus affected by maternal conditions that may be unrelated to present pregnancy(P00) | 258 | 9.3
… | All other causes | 323 | 11.6

… Category not applicable.

* Estimate does not meet National Center for Health Statistics standards of reliability.

^1^Includes fetal deaths to race and Hispanic-origin groups not shown separately.

^2^Race and Hispanic origin are reported separately on the report of fetal death; people of Hispanic origin may be of any race. In this table, non-Hispanic women are classified by race. Race categories are consistent with the 1997 Office of Management and Budget standards; see Technical Notes in this report. Single race is defined as only one race reported on the report of fetal death.

^3^Includes all people of Hispanic origin of any race; see Technical Notes.

NOTES: Findings exclude data for jurisdictions for which the cause of death was unspecified (P95) for 50% or more of records (Arizona, Georgia, Hawaii, Michigan, Mississippi, Nevada, New York [including New York City], North Dakota, Vermont, Virginia, and Wyoming). Also excludes data for California, which did not report cause of death based on the 2003 revision of the U.S. Standard Report of Fetal Death for the full year.

SOURCE: National Center for Health Statistics, National Vital Statistics System.

## References

1 Centers for Disease Control and Prevention. CDC WONDER. Fetal deaths information. Available from: https://wonder.cdc.gov/fetal.html.
2 National Center for Health Statistics. User guide to the 2023 fetal death public use file. 2024. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/fetaldeath/2023fetaluserguide.pdf.
3 Makelarski JA, Romitti PA, Caspers KM, Puzhankara S, McDowell BD, Piper KN. Use of active surveillance methodologies to examine over-reporting of stillbirths on fetal death certificates. Birth Defects Res A Clin Mol Teratol. 2011 Dec;91(12):1004–10. DOI: 10.1002/bdra.22856.21960514
4 Heuser CC, Hunn J, Varner M, Hossain S, Vered S, Silver RM. Correlation between stillbirth vital statistics and medical records. Obstet Gynecol. 2010 Dec;116(6):1296–1301. DOI: 10.1097/AOG.0b013e3181fb8838.21099594
5 Lydon-Rochelle MT, Cárdenas V, Nelson JL, Tomashek KM, Mueller BA, Easterling TR. Validity of maternal and perinatal risk factors reported on fetal death certificates. Am J Public Health. 2005 Nov;95(11):1948–51. DOI: 10.2105/AJPH.2004.044305.16195532
6 National Center for Health Statistics. Patient’s worksheet for the report of fetal death. 2019. Available from: https://www.cdc.gov/nchs/data/dvs/fetal-death-mother-worksheet-english-2019-508.pdf.
7 National Center for Health Statistics. Facility worksheet for the report of fetal death. 2019. Available from: https://www.cdc.gov/nchs/data/dvs/fetal-death-facility-worksheet-2019-508.pdf.
8 National Center for Health Statistics. Guide to completing the facility worksheets for the Certificate of Live Birth and Report of Fetal Death (2003 revision). 2022. Available from: https://www.cdc.gov/nchs/data/dvs/GuidetoCompleteFacilityWks.pdf.
9 National Center for Health Statistics. 2003 revision of the U.S. Standard Report of Fetal Death. Available from: https://www.cdc.gov/nchs/data/dvs/FDEATH11-03finalACC.pdf.
10 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist. 1997;62(210):58782–90.
11 MacDorman MF, Gregory ECW. Fetal and perinatal mortality: United States, 2013. Natl Vital Stat Rep. 2015 Jul;64(8):1–24.
12 World Health Organization. International statistical classification of diseases and related health problems, 10th revision. 2009.
13 National Center for Health Statistics. Instruction manual, part 9: ICD–10 cause-of-death lists for tabulating mortality statistics (updated September 2020 to include WHO updates to ICD–10 for data year 2019). 2020. Available from: https://www.cdc.gov/nchs/data/dvs/Part9InstructionManual2019-508.pdf.
14 National Center for Health Statistics. Model state vital statistics act and regulations, 1992 revision. Public Health Service, PHS 94–1115. 1994. Available from: https://www.cdc.gov/nchs/data/misc/mvsact92b.pdf.
15 Kowaleski J. State definitions and reporting requirements for live births, fetal deaths, and induced terminations of pregnancy. National Center for Health Statistics. 1997. Available from: https://www.cdc.gov/nchs/data/misc/itop97.pdf.
16 National Center for Health Statistics. Report of the Panel to Evaluate the U.S. Standard Certificates. 2000. Available from: https://archive.cdc.gov/www_cdc_gov/nchs/data/dvs/panelreport_acc.pdf.
17 Hoyert DL. Perinatal mortality in the United States: 1985–91. Vital Health Stat 20. 1995 Aug;(26):1–26.
18 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D, et al. National Center for Health Statistics data presentation standards for rates and counts. Vital Health Stat 2. 2023 Mar;(200):1–26. DOI: 10.15620/cdc:124368.
19 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF, et al. National Center for Health Statistics data presentation standards for proportions. Vital Health Stat 2. 2017 Aug;(175):1–22.
20 Gregory ECW, Valenzuela CP, Hoyert DL. Fetal Mortality: United States, 2022. Natl Vital Stat Rep. 2024 Sep;(9). DOI: 10.15620/cdc/158788.
21 Martin JA, Osterman MJK, Kirmeyer SE, Gregory ECW. Measuring gestational age in vital statistics data: Transitioning to the obstetric estimate. Natl Vital Stat Rep. 2015 Jun;64(5):1–20.
22 National Center for Health Statistics. Editing specifications for fetal death records [unpublished]. 2020.
23 National Center for Health Statistics. User guide to the 2017 fetal death public use file. 2019. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/fetaldeath/2017FetalUserGuide.pdf.
24 National Center for Health Statistics. User guide to the 2018 fetal death public use file. 2020. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/fetaldeath/2018FetalUserGuide.pdf.

## Technical Notes

### Definition of fetal death

Fetal death means “death prior to the complete expulsion or extraction from its mother of a product of human conception, irrespective of the duration of pregnancy and which is not an induced termination of pregnancy.” The death is indicated by the fact that after such expulsion or extraction, the fetus does not breathe or show any other evidence of life such as beating of the heart, pulsation of the umbilical cord, or definite movement of voluntary muscles. Heartbeats are to be distinguished from transient cardiac contractions; respirations are to be distinguished from fleeting respiratory efforts or gasps.

This definition (14) has been adopted by the Centers for Disease Control and Prevention, National Center for Health Statistics as the nationally recommended standard and is based on the definition published by the World Health Organization in 1950 and revised in 1988. The term fetal death is defined on an all-inclusive basis to end confusion arising from the use of such terms as stillbirth, spontaneous abortion, and miscarriage. All U.S. states and registration areas have definitions similar to the standard definition, except for Puerto Rico and Wisconsin, which have no formal definition (15). Fetal deaths do not include induced terminations of pregnancy.

### Reporting requirements for fetal death data

Variation exists among states in reporting requirements (2) and possibly in completeness of reporting for fetal death data, and this can have important implications for comparisons of fetal mortality rates by state. All jurisdictions require reporting of fetal deaths of at least 20 weeks of gestation or more, or a minimum birthweight of 350 grams (roughly equal to 20 weeks), or some combination of the two. However, six states, New York City, American Samoa, and U.S. Virgin Islands require reporting of fetal deaths at all periods of gestation, two states require reporting beginning at 12 weeks of gestation, and one state requires reporting beginning at 16 weeks of gestation. Areas that report fetal deaths at all periods of gestation appear to have a higher percentage of fetal deaths occurring at 20–27 weeks of gestation than those that begin reporting at later gestational ages. Table B presents fetal mortality rates for fetal deaths at 24 weeks of gestation or more for a combined 3-year period to better account for state differences in reporting requirements and to improve on the reliability of rates based on smaller numbers. Aside from this exception, this report presents data on fetal deaths with a stated or presumed period of gestation of 20 weeks or more.

### Percentage of unknown responses

In the tables in this report, unknown responses are shown in frequencies tables but are excluded from the computation of percent distributions and fetal mortality rates. As a result, rates published in this report by variables with a substantial percentage of unknown responses (such as birthweight) may understate the true rates of fetal mortality for that characteristic. In this report, tobacco use data for Hawaii are excluded due to a high percentage of unknown responses (60.0%).

### 2003 revision of U.S. Standard Report of Fetal Death

Data for 2018–2023 presented in this report are based on the 2003 revision of the U.S. Standard Report of Fetal Death; data for earlier years are based on both the 1989 and the 2003 fetal death report revisions. The 2003 revision is described in detail elsewhere (16).

### Computation of rates

Fetal mortality rates in this report are computed as the number of fetal deaths at 20 weeks of gestation or more per 1,000 live births and fetal deaths at 20 weeks or more. The denominators for all fetal mortality rates are live births plus fetal deaths in the specified gestational age group, to represent the population at risk of the event.

Fetal mortality rate = (Fetal deaths at 20 weeks of gestation or more)/(Live births and fetal deaths at 20 weeks or more) • 1 , 000 Equation 1 shows the formula used to calculate the fetal mortality rate. The fetal mortality rate equals the number of fetal deaths at 20 weeks of gestation or more divided by the number of live births plus the number of fetal deaths at 20 weeks of gestation or more multiplied by 1,000.

In each case, the fetal deaths included in the denominator of each rate mirror the fetal deaths included in the numerator. A previous National Center for Health Statistics report (17) contains information on the historical development of various perinatal measures.

### Presentation of counts, rates, and percentages

An asterisk (*) in the tables indicates that a count, rate, or percentage does not meet National Center for Health Statistics (NCHS) standards of reliability (18,19). Three separate criteria are used to determine if a count (number of events), rate, or proportion meets these standards (2).

### Presentation of counts and rates

New criteria for showing counts and rates were adopted by NCHS beginning with 2023 data (18). For counts, the number of deaths or births is shown depending on the count of deaths or births and on the relative width of the confidence interval of the count, based on a gamma distribution. Before the 2023 data year, the number of deaths or births was shown regardless of the count. For rates, whether a rate is shown depends on the count for the numerator and on the relative width of the confidence interval of the rate based on a Student’s t interval for the logarithm of the rate. Rates published for data years before 2023 were represented by an asterisk when the numerator was fewer than 20 deaths. For detailed information on the new criteria, see “National Center for Health Statistics Data Presentation Standards for Rates and Counts” (18).

### Presentation of percentages

For proportions (or percentages), new criteria were adopted by NCHS beginning with 2017 data but were only implemented for fetal deaths starting with 2023 data. For 2023 and later, a proportion (percentage) is shown based on the denominator size and on the absolute or relative widths of the confidence interval of the proportion or percentage calculated using the Clopper–Pearson method. Additionally, proportions or percentages based on fewer than 10 deaths in the numerator are represented with an asterisk. For earlier years, percentages were represented by an asterisk when the numerator was fewer than 20 deaths. For detailed information on these criteria, see “National Center for Health Statistics Data Presentation Standards for Proportions” (19).

### Hispanic origin and race

#### Hispanic origin

Hispanic origin and race are reported separately on the report of fetal death. Data are presented in some tables for specific Hispanic subgroups: Central and South American, Cuban, Dominican, Mexican, other and unknown Hispanic, and Puerto Rican. Data are presented separately for Dominican women beginning in 2018. Data for this subgroup had previously been included in the category other and unknown Hispanic. In tabulations of fetal death data by race and Hispanic origin, data for people of Hispanic origin are not further classified by race because most fetal deaths to Hispanic women are reported as White.

Beginning in 2022, fetal death records for which the mother’s detailed Hispanic origin is reported as “Latin American” are recoded to “other and unknown Hispanic origin” for the mother’s Hispanic origin recode shown in this report (2). In previous years, a record with a reported detailed Hispanic origin of Latin American was recoded to “Central and South American” (2). This change resulted in a substantial shift in the number of women reported in these two categories (20). Accordingly, fetal mortality rates calculated for these two groups are considered not comparable beginning with 2022.

#### Race

This report presents data on race and Hispanic origin based on the 1997 Office of Management and Budget standards (10). The 2003 revision of the U.S. Standard Report of Fetal Death requires the reporting of a minimum of five race categories and allows for the reporting of race either alone (single race) or in combination (more than one race or multiple races) for the mother (9), according to the Office of Management and Budget’s 1997 revised standards (10). The five categories for race specified in the revised standards are: American Indian and Alaska Native, Asian, Black or African American, Native Hawaiian or Other Pacific Islander, and White.

Beginning in 2018, all states and the District of Columbia, in addition to Guam, Northern Marianas, Puerto Rico, and U.S. Virgin Islands, were reporting race on fetal death reports according to the 1997 revised Office of Management and Budget’s standards. In 2023, 2.3% of women in the United States reported more than one race. Before 2018, the number of states that reported multiple-race information varied widely, increasing from 1 state in 2003 to all 50 states, District of Columbia, Guam, Northern Marianas, Puerto Rico, and U.S. Virgin Islands in 2018.

### Period of gestation

Beginning with the 2014 data year, the National Center for Health Statistics began using the obstetric estimate of gestation at delivery as the primary measure for estimating gestational age (21). Obstetric estimate of gestation at delivery data are edited for gestational ages that are clearly inconsistent with birthweight. If the obstetric estimate of gestation at delivery is not reported, or is inconsistent with birthweight, the last menstrual period-based gestational age is used (0.6% of fetal death records and 0.1% of live birth records in 2023). These procedures are described in more detail elsewhere (22).

See the “User Guide to the 2017 Fetal Death Data File” for a more detailed description of the transition and Table 1 of the “User Guide to the 2018 Fetal Death Data File” for trends in total, early, and late fetal mortality based on both the obstetric estimate of gestation at delivery and last menstrual period measures (23,24).

### Gestational age not stated

Fetal deaths with not-stated gestational age are presumed to be 20 weeks of gestation or more if the state requires reporting of all fetal deaths at 20 weeks or more, or if the fetus weighed 350 grams or more in those states requiring reporting of all fetal deaths regardless of gestational age. In Tables 1 and 4, fetal deaths with not-stated gestational age are allocated to the 20–27 weeks and 28 weeks or more categories according to the proportion of fetal deaths with stated gestational age that fall into each category (proportional distribution). Similarly, for Table B, fetal deaths with not-stated gestational age are proportionally distributed into the 20–23 weeks and 24 weeks or more categories. Proportional distribution is not performed for data in tables that show more detailed gestational age categories (Table 6). The allocation of not-stated gestational age for fetal deaths is made individually for each maternal age, race and Hispanic-origin group, and state in the computation of fetal mortality rates.

### Cause of death

Cause-of-death data are included for the 38 states and District of Columbia that reported cause of death based on the 2003 revision of the U.S. Standard Report of Fetal Death for the full year and met the reporting requirement of having less than 50% of records assigned to unspecified cause (P95) (cause-of-death data did not meet these requirements for Arizona, California, Georgia, Hawaii, Michigan, Mississippi, Nevada, New York [including New York City], North Dakota, Vermont, Virginia, and Wyoming).

### Random variation in fetal mortality

See the “User Guide to the 2023 Fetal Death Public Use File” (2) for more detailed information and formulas.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/email-updates.htm.

For questions or general information about NCHS: Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info

For more NCHS NVSRs, visit: https://www.cdc.gov/nchs/products/nvsr.htm.