# Volume 74 Number 6 United States Life Tables, 2023

### Objectives

This report presents complete period life tables for the United States by Hispanic origin and race and sex, based on age-specific death rates in 2023.

### Methods

Data used to prepare the 2023 life tables are 2023 final mortality statistics; July 1, 2023, population estimates based on the blended base population estimates produced by the U.S. Census Bureau; and 2023 Medicare data for people ages 66–99. The methodology used to estimate the life tables for the Hispanic population remains unchanged from that developed for the publication of life tables by Hispanic origin for data year 2006. The same methodology is used to estimate the life tables for the American Indian and Alaska Native non-Hispanic and Asian non-Hispanic populations. The methodology used to estimate the 2023 life tables for all other groups was first implemented with data year 2008.

### Results

In 2023, the overall expectation of life at birth was 78.4 years, increasing 0.9 year from 77.5 years in 2022. Between 2022 and 2023, life expectancy at birth increased by 1.0 year for males (from 74.8 to 75.8) and by 0.9 year for females (80.2 to 81.1). Between 2022 and 2023, life expectancy increased by 2.3 years for the American Indian and Alaska Native non-Hispanic population (67.8 to 70.1), by 1.3 years for the Hispanic population (80.0 to 81.3), by 1.2 years for the Black non-Hispanic population (72.8 to 74.0), by 0.9 year or the White non-Hispanic population (77.5 to 78.4), and by 0.8 year for the Asian non-Hispanic population (84.4 to 85.2).

## Introduction

Life tables are of two types: the cohort (or generation) life table and the period (or current) life table. The cohort life table presents the mortality experience of a particular birth cohort—all people born in the year 1900, for example—from the moment of birth through consecutive ages in successive calendar years. Based on age-specific death rates observed through consecutive calendar years, the cohort life table reflects the mortality experience of an actual cohort from birth until no lives remain in the group. To prepare just a single complete cohort life table requires data over many years. Constructing cohort life tables entirely based on observed data for real cohorts is usually not feasible, due to data unavailability or incompleteness (1). For example, a life table representation of the mortality experience of a cohort of people born in 1970 would require the use of data projection techniques to estimate deaths into the future (2,3).

The period life table presents what would happen to a hypothetical cohort if it experienced throughout its entire life the mortality conditions of a particular period in time. For example, a period life table for 2023 assumes a hypothetical cohort that is subject throughout its lifetime to the age-specific death rates prevailing for the actual population in 2023. Consequently, the period life table may be characterized as offering a “snapshot” of current mortality experience, showing the long-range implications of a set of age-specific death rates that prevailed in a given year. In this report, the term “life table” refers only to the period life table and not to the cohort life table.

Life tables can be classified in two ways according to the length of the age interval in which data are presented. A complete life table contains data for every single year of age. An abridged life table typically contains data by 5- or 10-year age intervals. A complete life table can easily be combined into 5- or 10-year age groups (see Technical Notes for instructions). Other than the decennial life tables, U.S. life tables based on data before 1997 are abridged life tables constructed by reference to a standard table (4).

Complete period life tables by Hispanic origin and race based on the 1997 Office of Management and Budget revised standards for the reporting of race and ethnicity are presented in this report (5). Race categories differ from the bridged-race categories shown in previous reports for years 2000–2017. Comparisons between data years 2000–2017 and 2018–2023 should be interpreted considering these differences. Life expectancy estimates for bridged-race categories are included in this report for years 2006–2020 to document the effect of the change in race standards and to show trends. Data year 2020 was the last year for which estimates for bridged-race categories were presented in this report. Hispanic origin is consistent with previous reports because the classification of Hispanic origin did not change between standards (5,6). In the remainder of this report, “race” refers to “single race” based on the 1997 standard (see Technical Notes and “Comparability of Race-specific Mortality Data Based on 1977 Versus 1997 Reporting Standards” for more information on differences between single- and bridged-race groups (7).

## Data and Methods

The data used to prepare the U.S. life tables for 2023 are final numbers of deaths for the year 2023; July 1, 2023, population estimates; and age-specific death and population counts for Medicare beneficiaries ages 66–99 for the year 2023 from the Centers for Medicare & Medicaid Services. Population estimates are based on the blended base produced by the U.S. Census Bureau instead of the April 1, 2020, decennial population count. The blended base consists of the blend of 2020 postcensal population estimates, based on the April 1, 2010, census; 2020 Demographic Analysis Estimates; and 2020 census data from the internal Census Edited File (see https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2023/methods-statement-v2023.pdf). Data from the Medicare program were used to supplement vital statistics and census data for ages 66 and over for the total, Black non-Hispanic, and White non-Hispanic populations. Because reliable Medicare data were not available for the Hispanic, American Indian and Alaska Native non-Hispanic, and Asian non-Hispanic populations, statistical modeling was used to produce reliable old-age mortality estimates for these groups. The U.S. life tables by Hispanic origin and race are based on death rates that have been adjusted for race and ethnicity misclassification on death certificates using classification ratios (or correction factors) generated from studies that evaluate Hispanic origin and race misclassification on death certificates in the United States (8–10). See Technical Notes for a detailed description of the data sets and methodology used to estimate the life tables and life table partitioning by cause of death.

### Expectation of life

The most frequently used life table statistic is life expectancy (e_x_), which is the average number of years of life remaining for people who have attained a given age (x). Life expectancy and other life table values for each age in 2023 are shown for the total population and by Hispanic origin and race and sex in Tables 1–18. Life expectancy is summarized by age, Hispanic origin and race, and sex in Table A.

Table 1

Life table for the total population: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table01.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.005588 | 100,000 | 559 | 99,515 | 7,842,141 | 78.4
1–2 | 0.000439 | 99,441 | 44 | 99,419 | 7,742,626 | 77.9
2–3 | 0.000283 | 99,398 | 28 | 99,384 | 7,643,207 | 76.9
3–4 | 0.000213 | 99,369 | 21 | 99,359 | 7,543,824 | 75.9
4–5 | 0.000161 | 99,348 | 16 | 99,340 | 7,444,465 | 74.9
5–6 | 0.000149 | 99,332 | 15 | 99,325 | 7,345,124 | 73.9
6–7 | 0.000136 | 99,317 | 13 | 99,311 | 7,245,799 | 73.0
7–8 | 0.000125 | 99,304 | 12 | 99,298 | 7,146,489 | 72.0
8–9 | 0.000113 | 99,292 | 11 | 99,286 | 7,047,191 | 71.0
9–10 | 0.000100 | 99,280 | 10 | 99,275 | 6,947,905 | 70.0
10–11 | 0.000092 | 99,271 | 9 | 99,266 | 6,848,629 | 69.0
11–12 | 0.000101 | 99,261 | 10 | 99,256 | 6,749,364 | 68.0
12–13 | 0.000137 | 99,251 | 14 | 99,245 | 6,650,107 | 67.0
13–14 | 0.000206 | 99,238 | 20 | 99,228 | 6,550,863 | 66.0
14–15 | 0.000299 | 99,217 | 30 | 99,203 | 6,451,635 | 65.0
15–16 | 0.000400 | 99,188 | 40 | 99,168 | 6,352,432 | 64.0
16–17 | 0.000497 | 99,148 | 49 | 99,123 | 6,253,265 | 63.1
17–18 | 0.000587 | 99,099 | 58 | 99,070 | 6,154,141 | 62.1
18–19 | 0.000666 | 99,041 | 66 | 99,008 | 6,055,072 | 61.1
19–20 | 0.000739 | 98,975 | 73 | 98,938 | 5,956,064 | 60.2
20–21 | 0.000817 | 98,901 | 81 | 98,861 | 5,857,126 | 59.2
21–22 | 0.000899 | 98,821 | 89 | 98,776 | 5,758,265 | 58.3
22–23 | 0.000971 | 98,732 | 96 | 98,684 | 5,659,489 | 57.3
23–24 | 0.001031 | 98,636 | 102 | 98,585 | 5,560,805 | 56.4
24–25 | 0.001081 | 98,534 | 106 | 98,481 | 5,462,220 | 55.4
25–26 | 0.001126 | 98,428 | 111 | 98,372 | 5,363,739 | 54.5
26–27 | 0.001177 | 98,317 | 116 | 98,259 | 5,265,367 | 53.6
27–28 | 0.001243 | 98,201 | 122 | 98,140 | 5,167,108 | 52.6
28–29 | 0.001327 | 98,079 | 130 | 98,014 | 5,068,967 | 51.7
29–30 | 0.001422 | 97,949 | 139 | 97,879 | 4,970,953 | 50.8
30–31 | 0.001520 | 97,810 | 149 | 97,735 | 4,873,074 | 49.8
31–32 | 0.001611 | 97,661 | 157 | 97,582 | 4,775,339 | 48.9
32–33 | 0.001693 | 97,504 | 165 | 97,421 | 4,677,756 | 48.0
33–34 | 0.001765 | 97,339 | 172 | 97,253 | 4,580,335 | 47.1
34–35 | 0.001834 | 97,167 | 178 | 97,078 | 4,483,082 | 46.1
35–36 | 0.001904 | 96,989 | 185 | 96,896 | 4,386,005 | 45.2
36–37 | 0.001983 | 96,804 | 192 | 96,708 | 4,289,109 | 44.3
37–38 | 0.002074 | 96,612 | 200 | 96,512 | 4,192,401 | 43.4
38–39 | 0.002179 | 96,412 | 210 | 96,307 | 4,095,889 | 42.5
39–40 | 0.002295 | 96,202 | 221 | 96,091 | 3,999,582 | 41.6
40–41 | 0.002424 | 95,981 | 233 | 95,864 | 3,903,491 | 40.7
41–42 | 0.002557 | 95,748 | 245 | 95,626 | 3,807,627 | 39.8
42–43 | 0.002678 | 95,503 | 256 | 95,375 | 3,712,001 | 38.9
43–44 | 0.002784 | 95,247 | 265 | 95,115 | 3,616,626 | 38.0
44–45 | 0.002888 | 94,982 | 274 | 94,845 | 3,521,511 | 37.1
45–46 | 0.003008 | 94,708 | 285 | 94,566 | 3,426,666 | 36.2
46–47 | 0.003163 | 94,423 | 299 | 94,274 | 3,332,100 | 35.3
47–48 | 0.003356 | 94,124 | 316 | 93,966 | 3,237,826 | 34.4
48–49 | 0.003586 | 93,809 | 336 | 93,640 | 3,143,860 | 33.5
49–50 | 0.003843 | 93,472 | 359 | 93,293 | 3,050,220 | 32.6
50–51 | 0.004120 | 93,113 | 384 | 92,921 | 2,956,927 | 31.8
51–52 | 0.004420 | 92,729 | 410 | 92,524 | 2,864,006 | 30.9
52–53 | 0.004752 | 92,319 | 439 | 92,100 | 2,771,481 | 30.0
53–54 | 0.005130 | 91,881 | 471 | 91,645 | 2,679,381 | 29.2
54–55 | 0.005562 | 91,409 | 508 | 91,155 | 2,587,736 | 28.3
55–56 | 0.006022 | 90,901 | 547 | 90,627 | 2,496,581 | 27.5
56–57 | 0.006524 | 90,354 | 589 | 90,059 | 2,405,954 | 26.6
57–58 | 0.007106 | 89,764 | 638 | 89,445 | 2,315,895 | 25.8
58–59 | 0.007769 | 89,126 | 692 | 88,780 | 2,226,450 | 25.0
59–60 | 0.008476 | 88,434 | 750 | 88,059 | 2,137,670 | 24.2
60–61 | 0.009202 | 87,684 | 807 | 87,281 | 2,049,611 | 23.4
61–62 | 0.009926 | 86,877 | 862 | 86,446 | 1,962,330 | 22.6
62–63 | 0.010656 | 86,015 | 917 | 85,557 | 1,875,884 | 21.8
63–64 | 0.011405 | 85,098 | 971 | 84,613 | 1,790,327 | 21.0
64–65 | 0.012197 | 84,128 | 1,026 | 83,615 | 1,705,714 | 20.3
65–66 | 0.013054 | 83,102 | 1,085 | 82,559 | 1,622,099 | 19.5
66–67 | 0.014088 | 82,017 | 1,155 | 81,439 | 1,539,540 | 18.8
67–68 | 0.015075 | 80,861 | 1,219 | 80,252 | 1,458,101 | 18.0
68–69 | 0.016150 | 79,642 | 1,286 | 78,999 | 1,377,849 | 17.3
69–70 | 0.017324 | 78,356 | 1,357 | 77,678 | 1,298,849 | 16.6
70–71 | 0.018460 | 76,999 | 1,421 | 76,288 | 1,221,172 | 15.9
71–72 | 0.019921 | 75,577 | 1,506 | 74,825 | 1,144,884 | 15.1
72–73 | 0.021541 | 74,072 | 1,596 | 73,274 | 1,070,059 | 14.4
73–74 | 0.023476 | 72,476 | 1,701 | 71,626 | 996,785 | 13.8
74–75 | 0.025685 | 70,775 | 1,818 | 69,866 | 925,160 | 13.1
75–76 | 0.028219 | 68,957 | 1,946 | 67,984 | 855,294 | 12.4
76–77 | 0.030546 | 67,011 | 2,047 | 65,988 | 787,310 | 11.7
77–78 | 0.034523 | 64,964 | 2,243 | 63,843 | 721,322 | 11.1
78–79 | 0.037655 | 62,721 | 2,362 | 61,540 | 657,479 | 10.5
79–80 | 0.042211 | 60,360 | 2,548 | 59,086 | 595,939 | 9.9
80–81 | 0.046538 | 57,812 | 2,690 | 56,466 | 536,853 | 9.3
81–82 | 0.052311 | 55,121 | 2,883 | 53,680 | 480,387 | 8.7
82–83 | 0.058338 | 52,238 | 3,047 | 50,714 | 426,707 | 8.2
83–84 | 0.064645 | 49,190 | 3,180 | 47,600 | 375,993 | 7.6
84–85 | 0.071961 | 46,010 | 3,311 | 44,355 | 328,393 | 7.1
85–86 | 0.079677 | 42,699 | 3,402 | 40,998 | 284,038 | 6.7
86–87 | 0.089580 | 39,297 | 3,520 | 37,537 | 243,040 | 6.2
87–88 | 0.100503 | 35,777 | 3,596 | 33,979 | 205,502 | 5.7
88–89 | 0.112498 | 32,181 | 3,620 | 30,371 | 171,523 | 5.3
89–90 | 0.125607 | 28,561 | 3,587 | 26,767 | 141,152 | 4.9
90–91 | 0.139858 | 24,974 | 3,493 | 23,227 | 114,385 | 4.6
91–92 | 0.155262 | 21,481 | 3,335 | 19,813 | 91,158 | 4.2
92–93 | 0.171809 | 18,146 | 3,118 | 16,587 | 71,344 | 3.9
93–94 | 0.189467 | 15,028 | 2,847 | 13,604 | 54,757 | 3.6
94–95 | 0.208176 | 12,181 | 2,536 | 10,913 | 41,153 | 3.4
95–96 | 0.227850 | 9,645 | 2,198 | 8,546 | 30,240 | 3.1
96–97 | 0.248376 | 7,447 | 1,850 | 6,523 | 21,694 | 2.9
97–98 | 0.269615 | 5,598 | 1,509 | 4,843 | 15,172 | 2.7
98–99 | 0.291405 | 4,088 | 1,191 | 3,493 | 10,328 | 2.5
99–100 | 0.313565 | 2,897 | 908 | 2,443 | 6,836 | 2.4
100 and older | 1.000000 | 1,989 | 1,989 | 4,393 | 4,393 | 2.2

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 2

Life table for males: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table02.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.006023 | 100,000 | 602 | 99,477 | 7,581,780 | 75.8
1–2 | 0.000481 | 99,398 | 48 | 99,374 | 7,482,304 | 75.3
2–3 | 0.000332 | 99,350 | 33 | 99,333 | 7,382,930 | 74.3
3–4 | 0.000237 | 99,317 | 24 | 99,305 | 7,283,597 | 73.3
4–5 | 0.000179 | 99,293 | 18 | 99,284 | 7,184,291 | 72.4
5–6 | 0.000165 | 99,275 | 16 | 99,267 | 7,085,007 | 71.4
6–7 | 0.000151 | 99,259 | 15 | 99,252 | 6,985,740 | 70.4
7–8 | 0.000139 | 99,244 | 14 | 99,237 | 6,886,488 | 69.4
8–9 | 0.000122 | 99,230 | 12 | 99,224 | 6,787,251 | 68.4
9–10 | 0.000101 | 99,218 | 10 | 99,213 | 6,688,027 | 67.4
10–11 | 0.000087 | 99,208 | 9 | 99,204 | 6,588,814 | 66.4
11–12 | 0.000097 | 99,200 | 10 | 99,195 | 6,489,610 | 65.4
12–13 | 0.000150 | 99,190 | 15 | 99,182 | 6,390,415 | 64.4
13–14 | 0.000256 | 99,175 | 25 | 99,162 | 6,291,233 | 63.4
14–15 | 0.000397 | 99,150 | 39 | 99,130 | 6,192,070 | 62.5
15–16 | 0.000551 | 99,110 | 55 | 99,083 | 6,092,940 | 61.5
16–17 | 0.000698 | 99,056 | 69 | 99,021 | 5,993,857 | 60.5
17–18 | 0.000833 | 98,987 | 82 | 98,945 | 5,894,836 | 59.6
18–19 | 0.000953 | 98,904 | 94 | 98,857 | 5,795,891 | 58.6
19–20 | 0.001061 | 98,810 | 105 | 98,757 | 5,697,034 | 57.7
20–21 | 0.001175 | 98,705 | 116 | 98,647 | 5,598,276 | 56.7
21–22 | 0.001295 | 98,589 | 128 | 98,525 | 5,499,629 | 55.8
22–23 | 0.001401 | 98,461 | 138 | 98,392 | 5,401,104 | 54.9
23–24 | 0.001487 | 98,323 | 146 | 98,250 | 5,302,712 | 53.9
24–25 | 0.001560 | 98,177 | 153 | 98,101 | 5,204,461 | 53.0
25–26 | 0.001625 | 98,024 | 159 | 97,944 | 5,106,361 | 52.1
26–27 | 0.001697 | 97,865 | 166 | 97,782 | 5,008,416 | 51.2
27–28 | 0.001783 | 97,699 | 174 | 97,612 | 4,910,634 | 50.3
28–29 | 0.001890 | 97,525 | 184 | 97,432 | 4,813,023 | 49.4
29–30 | 0.002008 | 97,340 | 195 | 97,242 | 4,715,590 | 48.4
30–31 | 0.002127 | 97,145 | 207 | 97,041 | 4,618,348 | 47.5
31–32 | 0.002237 | 96,938 | 217 | 96,830 | 4,521,307 | 46.6
32–33 | 0.002336 | 96,721 | 226 | 96,608 | 4,424,477 | 45.7
33–34 | 0.002423 | 96,495 | 234 | 96,378 | 4,327,869 | 44.9
34–35 | 0.002505 | 96,262 | 241 | 96,141 | 4,231,490 | 44.0
35–36 | 0.002588 | 96,020 | 248 | 95,896 | 4,135,349 | 43.1
36–37 | 0.002680 | 95,772 | 257 | 95,644 | 4,039,453 | 42.2
37–38 | 0.002784 | 95,515 | 266 | 95,382 | 3,943,809 | 41.3
38–39 | 0.002903 | 95,249 | 277 | 95,111 | 3,848,427 | 40.4
39–40 | 0.003032 | 94,973 | 288 | 94,829 | 3,753,316 | 39.5
40–41 | 0.003176 | 94,685 | 301 | 94,535 | 3,658,487 | 38.6
41–42 | 0.003326 | 94,384 | 314 | 94,227 | 3,563,952 | 37.8
42–43 | 0.003464 | 94,070 | 326 | 93,907 | 3,469,725 | 36.9
43–44 | 0.003588 | 93,744 | 336 | 93,576 | 3,375,818 | 36.0
44–45 | 0.003714 | 93,408 | 347 | 93,235 | 3,282,242 | 35.1
45–46 | 0.003862 | 93,061 | 359 | 92,881 | 3,189,007 | 34.3
46–47 | 0.004052 | 92,702 | 376 | 92,514 | 3,096,126 | 33.4
47–48 | 0.004284 | 92,326 | 396 | 92,128 | 3,003,612 | 32.5
48–49 | 0.004557 | 91,931 | 419 | 91,721 | 2,911,483 | 31.7
49–50 | 0.004859 | 91,512 | 445 | 91,289 | 2,819,762 | 30.8
50–51 | 0.005182 | 91,067 | 472 | 90,831 | 2,728,473 | 30.0
51–52 | 0.005535 | 90,595 | 501 | 90,344 | 2,637,642 | 29.1
52–53 | 0.005938 | 90,094 | 535 | 89,826 | 2,547,297 | 28.3
53–54 | 0.006411 | 89,559 | 574 | 89,272 | 2,457,471 | 27.4
54–55 | 0.006960 | 88,985 | 619 | 88,675 | 2,368,200 | 26.6
55–56 | 0.007549 | 88,365 | 667 | 88,032 | 2,279,525 | 25.8
56–57 | 0.008183 | 87,698 | 718 | 87,339 | 2,191,493 | 25.0
57–58 | 0.008909 | 86,981 | 775 | 86,593 | 2,104,154 | 24.2
58–59 | 0.009721 | 86,206 | 838 | 85,787 | 2,017,561 | 23.4
59–60 | 0.010581 | 85,368 | 903 | 84,916 | 1,931,774 | 22.6
60–61 | 0.011457 | 84,464 | 968 | 83,980 | 1,846,858 | 21.9
61–62 | 0.012333 | 83,497 | 1,030 | 82,982 | 1,762,877 | 21.1
62–63 | 0.013223 | 82,467 | 1,090 | 81,922 | 1,679,896 | 20.4
63–64 | 0.014147 | 81,376 | 1,151 | 80,801 | 1,597,974 | 19.6
64–65 | 0.015132 | 80,225 | 1,214 | 79,618 | 1,517,173 | 18.9
65–66 | 0.016196 | 79,011 | 1,280 | 78,371 | 1,437,555 | 18.2
66–67 | 0.017494 | 77,732 | 1,360 | 77,052 | 1,359,184 | 17.5
67–68 | 0.018695 | 76,372 | 1,428 | 75,658 | 1,282,132 | 16.8
68–69 | 0.019985 | 74,944 | 1,498 | 74,195 | 1,206,474 | 16.1
69–70 | 0.021360 | 73,446 | 1,569 | 72,662 | 1,132,279 | 15.4
70–71 | 0.022642 | 71,877 | 1,627 | 71,064 | 1,059,617 | 14.7
71–72 | 0.024317 | 70,250 | 1,708 | 69,396 | 988,554 | 14.1
72–73 | 0.026170 | 68,542 | 1,794 | 67,645 | 919,158 | 13.4
73–74 | 0.028328 | 66,748 | 1,891 | 65,802 | 851,513 | 12.8
74–75 | 0.030787 | 64,857 | 1,997 | 63,859 | 785,711 | 12.1
75–76 | 0.033522 | 62,860 | 2,107 | 61,807 | 721,852 | 11.5
76–77 | 0.036028 | 60,753 | 2,189 | 59,659 | 660,045 | 10.9
77–78 | 0.040607 | 58,564 | 2,378 | 57,375 | 600,387 | 10.3
78–79 | 0.044020 | 56,186 | 2,473 | 54,950 | 543,012 | 9.7
79–80 | 0.049348 | 53,713 | 2,651 | 52,388 | 488,062 | 9.1
80–81 | 0.054164 | 51,062 | 2,766 | 49,679 | 435,674 | 8.5
81–82 | 0.061040 | 48,297 | 2,948 | 46,822 | 385,995 | 8.0
82–83 | 0.068034 | 45,348 | 3,085 | 43,806 | 339,173 | 7.5
83–84 | 0.075182 | 42,263 | 3,177 | 40,675 | 295,367 | 7.0
84–85 | 0.082862 | 39,086 | 3,239 | 37,466 | 254,692 | 6.5
85–86 | 0.092160 | 35,847 | 3,304 | 34,195 | 217,226 | 6.1
86–87 | 0.103004 | 32,543 | 3,352 | 30,867 | 183,030 | 5.6
87–88 | 0.115464 | 29,191 | 3,371 | 27,506 | 152,163 | 5.2
88–89 | 0.129086 | 25,821 | 3,333 | 24,154 | 124,657 | 4.8
89–90 | 0.143895 | 22,488 | 3,236 | 20,870 | 100,503 | 4.5
90–91 | 0.159898 | 19,252 | 3,078 | 17,713 | 79,633 | 4.1
91–92 | 0.177078 | 16,173 | 2,864 | 14,742 | 61,920 | 3.8
92–93 | 0.195392 | 13,310 | 2,601 | 12,009 | 47,179 | 3.5
93–94 | 0.214769 | 10,709 | 2,300 | 9,559 | 35,170 | 3.3
94–95 | 0.235109 | 8,409 | 1,977 | 7,420 | 25,611 | 3.0
95–96 | 0.256283 | 6,432 | 1,648 | 5,608 | 18,190 | 2.8
96–97 | 0.278136 | 4,784 | 1,330 | 4,118 | 12,582 | 2.6
97–98 | 0.300487 | 3,453 | 1,038 | 2,934 | 8,464 | 2.5
98–99 | 0.323140 | 2,415 | 781 | 2,025 | 5,530 | 2.3
99–100 | 0.345888 | 1,635 | 566 | 1,352 | 3,505 | 2.1
100 and older | 1.000000 | 1,069 | 1,069 | 2,152 | 2,152 | 2.0

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 3

Life table for females: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table03.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.005132 | 100,000 | 513 | 99,555 | 8,107,991 | 81.1
1–2 | 0.000394 | 99,487 | 39 | 99,467 | 8,008,436 | 80.5
2–3 | 0.000232 | 99,448 | 23 | 99,436 | 7,908,969 | 79.5
3–4 | 0.000187 | 99,424 | 19 | 99,415 | 7,809,533 | 78.5
4–5 | 0.000142 | 99,406 | 14 | 99,399 | 7,710,118 | 77.6
5–6 | 0.000133 | 99,392 | 13 | 99,385 | 7,610,719 | 76.6
6–7 | 0.000119 | 99,379 | 12 | 99,373 | 7,511,334 | 75.6
7–8 | 0.000110 | 99,367 | 11 | 99,361 | 7,411,961 | 74.6
8–9 | 0.000103 | 99,356 | 10 | 99,351 | 7,312,600 | 73.6
9–10 | 0.000098 | 99,346 | 10 | 99,341 | 7,213,249 | 72.6
10–11 | 0.000098 | 99,336 | 10 | 99,331 | 7,113,908 | 71.6
11–12 | 0.000104 | 99,326 | 10 | 99,321 | 7,014,578 | 70.6
12–13 | 0.000123 | 99,316 | 12 | 99,310 | 6,915,257 | 69.6
13–14 | 0.000155 | 99,304 | 15 | 99,296 | 6,815,947 | 68.6
14–15 | 0.000196 | 99,288 | 19 | 99,278 | 6,716,651 | 67.6
15–16 | 0.000241 | 99,269 | 24 | 99,257 | 6,617,373 | 66.7
16–17 | 0.000286 | 99,245 | 28 | 99,231 | 6,518,116 | 65.7
17–18 | 0.000328 | 99,216 | 33 | 99,200 | 6,418,885 | 64.7
18–19 | 0.000366 | 99,184 | 36 | 99,166 | 6,319,685 | 63.7
19–20 | 0.000402 | 99,147 | 40 | 99,127 | 6,220,520 | 62.7
20–21 | 0.000443 | 99,108 | 44 | 99,086 | 6,121,392 | 61.8
21–22 | 0.000486 | 99,064 | 48 | 99,040 | 6,022,307 | 60.8
22–23 | 0.000524 | 99,016 | 52 | 98,990 | 5,923,267 | 59.8
23–24 | 0.000555 | 98,964 | 55 | 98,936 | 5,824,277 | 58.9
24–25 | 0.000583 | 98,909 | 58 | 98,880 | 5,725,341 | 57.9
25–26 | 0.000609 | 98,851 | 60 | 98,821 | 5,626,461 | 56.9
26–27 | 0.000640 | 98,791 | 63 | 98,759 | 5,527,640 | 56.0
27–28 | 0.000685 | 98,728 | 68 | 98,694 | 5,428,881 | 55.0
28–29 | 0.000748 | 98,660 | 74 | 98,623 | 5,330,187 | 54.0
29–30 | 0.000821 | 98,586 | 81 | 98,546 | 5,231,564 | 53.1
30–31 | 0.000898 | 98,505 | 88 | 98,461 | 5,133,019 | 52.1
31–32 | 0.000971 | 98,417 | 96 | 98,369 | 5,034,558 | 51.2
32–33 | 0.001037 | 98,321 | 102 | 98,270 | 4,936,189 | 50.2
33–34 | 0.001094 | 98,219 | 108 | 98,165 | 4,837,919 | 49.3
34–35 | 0.001149 | 98,112 | 113 | 98,055 | 4,739,753 | 48.3
35–36 | 0.001206 | 97,999 | 118 | 97,940 | 4,641,698 | 47.4
36–37 | 0.001270 | 97,881 | 124 | 97,819 | 4,543,758 | 46.4
37–38 | 0.001348 | 97,756 | 132 | 97,691 | 4,445,940 | 45.5
38–39 | 0.001441 | 97,625 | 141 | 97,554 | 4,348,249 | 44.5
39–40 | 0.001544 | 97,484 | 151 | 97,409 | 4,250,695 | 43.6
40–41 | 0.001660 | 97,333 | 162 | 97,253 | 4,153,286 | 42.7
41–42 | 0.001778 | 97,172 | 173 | 97,085 | 4,056,034 | 41.7
42–43 | 0.001883 | 96,999 | 183 | 96,908 | 3,958,948 | 40.8
43–44 | 0.001973 | 96,816 | 191 | 96,721 | 3,862,040 | 39.9
44–45 | 0.002057 | 96,625 | 199 | 96,526 | 3,765,320 | 39.0
45–46 | 0.002153 | 96,427 | 208 | 96,323 | 3,668,794 | 38.0
46–47 | 0.002277 | 96,219 | 219 | 96,109 | 3,572,471 | 37.1
47–48 | 0.002433 | 96,000 | 234 | 95,883 | 3,476,362 | 36.2
48–49 | 0.002621 | 95,766 | 251 | 95,641 | 3,380,479 | 35.3
49–50 | 0.002832 | 95,515 | 271 | 95,380 | 3,284,838 | 34.4
50–51 | 0.003062 | 95,245 | 292 | 95,099 | 3,189,458 | 33.5
51–52 | 0.003309 | 94,953 | 314 | 94,796 | 3,094,359 | 32.6
52–53 | 0.003572 | 94,639 | 338 | 94,470 | 2,999,563 | 31.7
53–54 | 0.003858 | 94,301 | 364 | 94,119 | 2,905,093 | 30.8
54–55 | 0.004179 | 93,937 | 393 | 93,741 | 2,810,974 | 29.9
55–56 | 0.004519 | 93,545 | 423 | 93,333 | 2,717,233 | 29.0
56–57 | 0.004897 | 93,122 | 456 | 92,894 | 2,623,900 | 28.2
57–58 | 0.005348 | 92,666 | 496 | 92,418 | 2,531,006 | 27.3
58–59 | 0.005873 | 92,170 | 541 | 91,900 | 2,438,588 | 26.5
59–60 | 0.006443 | 91,629 | 590 | 91,334 | 2,346,689 | 25.6
60–61 | 0.007034 | 91,038 | 640 | 90,718 | 2,255,355 | 24.8
61–62 | 0.007625 | 90,398 | 689 | 90,054 | 2,164,637 | 23.9
62–63 | 0.008216 | 89,709 | 737 | 89,340 | 2,074,583 | 23.1
63–64 | 0.008816 | 88,972 | 784 | 88,580 | 1,985,243 | 22.3
64–65 | 0.009448 | 88,187 | 833 | 87,771 | 1,896,663 | 21.5
65–66 | 0.010135 | 87,354 | 885 | 86,912 | 1,808,892 | 20.7
66–67 | 0.010961 | 86,469 | 948 | 85,995 | 1,721,981 | 19.9
67–68 | 0.011782 | 85,521 | 1,008 | 85,017 | 1,635,986 | 19.1
68–69 | 0.012696 | 84,514 | 1,073 | 83,977 | 1,550,968 | 18.4
69–70 | 0.013728 | 83,441 | 1,145 | 82,868 | 1,466,991 | 17.6
70–71 | 0.014755 | 82,295 | 1,214 | 81,688 | 1,384,124 | 16.8
71–72 | 0.016066 | 81,081 | 1,303 | 80,429 | 1,302,436 | 16.1
72–73 | 0.017524 | 79,778 | 1,398 | 79,079 | 1,222,006 | 15.3
73–74 | 0.019299 | 78,380 | 1,513 | 77,624 | 1,142,927 | 14.6
74–75 | 0.021326 | 76,867 | 1,639 | 76,048 | 1,065,303 | 13.9
75–76 | 0.023712 | 75,228 | 1,784 | 74,336 | 989,255 | 13.2
76–77 | 0.025914 | 73,444 | 1,903 | 72,493 | 914,919 | 12.5
77–78 | 0.029447 | 71,541 | 2,107 | 70,488 | 842,426 | 11.8
78–79 | 0.032420 | 69,434 | 2,251 | 68,309 | 771,939 | 11.1
79–80 | 0.036450 | 67,183 | 2,449 | 65,959 | 703,630 | 10.5
80–81 | 0.040493 | 64,735 | 2,621 | 63,424 | 637,671 | 9.9
81–82 | 0.045557 | 62,113 | 2,830 | 60,698 | 574,247 | 9.2
82–83 | 0.051025 | 59,284 | 3,025 | 57,771 | 513,548 | 8.7
83–84 | 0.056904 | 56,259 | 3,201 | 54,658 | 455,777 | 8.1
84–85 | 0.064118 | 53,057 | 3,402 | 51,356 | 401,119 | 7.6
85–86 | 0.070931 | 49,655 | 3,522 | 47,894 | 349,763 | 7.0
86–87 | 0.080253 | 46,133 | 3,702 | 44,282 | 301,868 | 6.5
87–88 | 0.090614 | 42,431 | 3,845 | 40,508 | 257,586 | 6.1
88–89 | 0.102080 | 38,586 | 3,939 | 36,617 | 217,078 | 5.6
89–90 | 0.114707 | 34,647 | 3,974 | 32,660 | 180,461 | 5.2
90–91 | 0.128541 | 30,673 | 3,943 | 28,702 | 147,801 | 4.8
91–92 | 0.143609 | 26,730 | 3,839 | 24,811 | 119,100 | 4.5
92–93 | 0.159919 | 22,892 | 3,661 | 21,061 | 94,289 | 4.1
93–94 | 0.177452 | 19,231 | 3,413 | 17,524 | 73,228 | 3.8
94–95 | 0.196164 | 15,818 | 3,103 | 14,267 | 55,703 | 3.5
95–96 | 0.215977 | 12,715 | 2,746 | 11,342 | 41,436 | 3.3
96–97 | 0.236785 | 9,969 | 2,361 | 8,789 | 30,094 | 3.0
97–98 | 0.258448 | 7,609 | 1,966 | 6,625 | 21,306 | 2.8
98–99 | 0.280798 | 5,642 | 1,584 | 4,850 | 14,680 | 2.6
99–100 | 0.303644 | 4,058 | 1,232 | 3,442 | 9,830 | 2.4
100 and older | 1.000000 | 2,826 | 2,826 | 6,389 | 6,389 | 2.3

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 4

Life table for the Hispanic population: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table04.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.005030 | 100,000 | 503 | 99,557 | 8,128,213 | 81.3
1–2 | 0.000371 | 99,497 | 37 | 99,479 | 8,028,656 | 80.7
2–3 | 0.000230 | 99,460 | 23 | 99,449 | 7,929,178 | 79.7
3–4 | 0.000174 | 99,437 | 17 | 99,429 | 7,829,729 | 78.7
4–5 | 0.000136 | 99,420 | 14 | 99,413 | 7,730,301 | 77.8
5–6 | 0.000121 | 99,406 | 12 | 99,400 | 7,630,888 | 76.8
6–7 | 0.000111 | 99,394 | 11 | 99,389 | 7,531,487 | 75.8
7–8 | 0.000103 | 99,383 | 10 | 99,378 | 7,432,098 | 74.8
8–9 | 0.000092 | 99,373 | 9 | 99,368 | 7,332,720 | 73.8
9–10 | 0.000080 | 99,364 | 8 | 99,360 | 7,233,352 | 72.8
10–11 | 0.000072 | 99,356 | 7 | 99,352 | 7,133,992 | 71.8
11–12 | 0.000079 | 99,349 | 8 | 99,345 | 7,034,640 | 70.8
12–13 | 0.000114 | 99,341 | 11 | 99,335 | 6,935,295 | 69.8
13–14 | 0.000182 | 99,330 | 18 | 99,321 | 6,835,960 | 68.8
14–15 | 0.000272 | 99,312 | 27 | 99,298 | 6,736,639 | 67.8
15–16 | 0.000371 | 99,285 | 37 | 99,266 | 6,637,341 | 66.9
16–17 | 0.000464 | 99,248 | 46 | 99,225 | 6,538,075 | 65.9
17–18 | 0.000550 | 99,202 | 55 | 99,174 | 6,438,850 | 64.9
18–19 | 0.000625 | 99,147 | 62 | 99,116 | 6,339,676 | 63.9
19–20 | 0.000694 | 99,085 | 69 | 99,051 | 6,240,559 | 63.0
20–21 | 0.000766 | 99,017 | 76 | 98,979 | 6,141,508 | 62.0
21–22 | 0.000844 | 98,941 | 84 | 98,899 | 6,042,530 | 61.1
22–23 | 0.000922 | 98,857 | 91 | 98,812 | 5,943,631 | 60.1
23–24 | 0.000995 | 98,766 | 98 | 98,717 | 5,844,819 | 59.2
24–25 | 0.001063 | 98,668 | 105 | 98,615 | 5,746,102 | 58.2
25–26 | 0.001130 | 98,563 | 111 | 98,507 | 5,647,487 | 57.3
26–27 | 0.001196 | 98,452 | 118 | 98,393 | 5,548,980 | 56.4
27–28 | 0.001260 | 98,334 | 124 | 98,272 | 5,450,587 | 55.4
28–29 | 0.001319 | 98,210 | 130 | 98,145 | 5,352,315 | 54.5
29–30 | 0.001373 | 98,080 | 135 | 98,013 | 5,254,170 | 53.6
30–31 | 0.001425 | 97,946 | 140 | 97,876 | 5,156,157 | 52.6
31–32 | 0.001474 | 97,806 | 144 | 97,734 | 5,058,281 | 51.7
32–33 | 0.001518 | 97,662 | 148 | 97,588 | 4,960,547 | 50.8
33–34 | 0.001558 | 97,514 | 152 | 97,438 | 4,862,959 | 49.9
34–35 | 0.001596 | 97,362 | 155 | 97,284 | 4,765,521 | 48.9
35–36 | 0.001634 | 97,206 | 159 | 97,127 | 4,668,237 | 48.0
36–37 | 0.001675 | 97,048 | 163 | 96,966 | 4,571,110 | 47.1
37–38 | 0.001725 | 96,885 | 167 | 96,801 | 4,474,144 | 46.2
38–39 | 0.001786 | 96,718 | 173 | 96,632 | 4,377,342 | 45.3
39–40 | 0.001855 | 96,545 | 179 | 96,456 | 4,280,711 | 44.3
40–41 | 0.001930 | 96,366 | 186 | 96,273 | 4,184,255 | 43.4
41–42 | 0.002008 | 96,180 | 193 | 96,083 | 4,087,982 | 42.5
42–43 | 0.002089 | 95,987 | 200 | 95,887 | 3,991,899 | 41.6
43–44 | 0.002174 | 95,786 | 208 | 95,682 | 3,896,012 | 40.7
44–45 | 0.002268 | 95,578 | 217 | 95,470 | 3,800,330 | 39.8
45–46 | 0.002374 | 95,361 | 226 | 95,248 | 3,704,860 | 38.9
46–47 | 0.002495 | 95,135 | 237 | 95,016 | 3,609,612 | 37.9
47–48 | 0.002632 | 94,898 | 250 | 94,773 | 3,514,595 | 37.0
48–49 | 0.002783 | 94,648 | 263 | 94,516 | 3,419,823 | 36.1
49–50 | 0.002949 | 94,384 | 278 | 94,245 | 3,325,306 | 35.2
50–51 | 0.003129 | 94,106 | 294 | 93,959 | 3,231,061 | 34.3
51–52 | 0.003329 | 93,812 | 312 | 93,656 | 3,137,102 | 33.4
52–53 | 0.003562 | 93,499 | 333 | 93,333 | 3,043,447 | 32.6
53–54 | 0.003836 | 93,166 | 357 | 92,988 | 2,950,114 | 31.7
54–55 | 0.004151 | 92,809 | 385 | 92,616 | 2,857,126 | 30.8
55–56 | 0.004492 | 92,424 | 415 | 92,216 | 2,764,510 | 29.9
56–57 | 0.004858 | 92,009 | 447 | 91,785 | 2,672,294 | 29.0
57–58 | 0.005276 | 91,562 | 483 | 91,320 | 2,580,509 | 28.2
58–59 | 0.005751 | 91,078 | 524 | 90,817 | 2,489,189 | 27.3
59–60 | 0.006274 | 90,555 | 568 | 90,271 | 2,398,372 | 26.5
60–61 | 0.006852 | 89,987 | 617 | 89,678 | 2,308,102 | 25.6
61–62 | 0.007455 | 89,370 | 666 | 89,037 | 2,218,423 | 24.8
62–63 | 0.008041 | 88,704 | 713 | 88,347 | 2,129,387 | 24.0
63–64 | 0.008588 | 87,990 | 756 | 87,613 | 2,041,039 | 23.2
64–65 | 0.009120 | 87,235 | 796 | 86,837 | 1,953,427 | 22.4
65–66 | 0.009676 | 86,439 | 836 | 86,021 | 1,866,590 | 21.6
66–67 | 0.010311 | 85,603 | 883 | 85,161 | 1,780,569 | 20.8
67–68 | 0.011061 | 84,720 | 937 | 84,252 | 1,695,407 | 20.0
68–69 | 0.011970 | 83,783 | 1,003 | 83,282 | 1,611,156 | 19.2
69–70 | 0.013034 | 82,780 | 1,079 | 82,241 | 1,527,874 | 18.5
70–71 | 0.014246 | 81,701 | 1,164 | 81,119 | 1,445,634 | 17.7
71–72 | 0.015573 | 80,537 | 1,254 | 79,910 | 1,364,514 | 16.9
72–73 | 0.016986 | 79,283 | 1,347 | 78,610 | 1,284,604 | 16.2
73–74 | 0.018442 | 77,936 | 1,437 | 77,218 | 1,205,995 | 15.5
74–75 | 0.019968 | 76,499 | 1,528 | 75,735 | 1,128,777 | 14.8
75–76 | 0.021608 | 74,971 | 1,620 | 74,161 | 1,053,042 | 14.0
76–77 | 0.023450 | 73,351 | 1,720 | 72,491 | 978,880 | 13.3
77–78 | 0.025948 | 71,631 | 1,859 | 70,702 | 906,389 | 12.7
78–79 | 0.028633 | 69,773 | 1,998 | 68,774 | 835,687 | 12.0
79–80 | 0.032129 | 67,775 | 2,178 | 66,686 | 766,913 | 11.3
80–81 | 0.035595 | 65,597 | 2,335 | 64,430 | 700,227 | 10.7
81–82 | 0.040131 | 63,262 | 2,539 | 61,993 | 635,797 | 10.1
82–83 | 0.044921 | 60,724 | 2,728 | 59,360 | 573,804 | 9.4
83–84 | 0.049930 | 57,996 | 2,896 | 56,548 | 514,444 | 8.9
84–85 | 0.055698 | 55,100 | 3,069 | 53,566 | 457,896 | 8.3
85–86 | 0.061374 | 52,031 | 3,193 | 50,435 | 404,330 | 7.8
86–87 | 0.069340 | 48,838 | 3,386 | 47,145 | 353,896 | 7.2
87–88 | 0.078189 | 45,451 | 3,554 | 43,675 | 306,751 | 6.7
88–89 | 0.087977 | 41,898 | 3,686 | 40,055 | 263,077 | 6.3
89–90 | 0.098756 | 38,212 | 3,774 | 36,325 | 223,022 | 5.8
90–91 | 0.110566 | 34,438 | 3,808 | 32,534 | 186,697 | 5.4
91–92 | 0.123437 | 30,630 | 3,781 | 28,740 | 154,163 | 5.0
92–93 | 0.137378 | 26,849 | 3,689 | 25,005 | 125,424 | 4.7
93–94 | 0.152384 | 23,161 | 3,529 | 21,396 | 100,418 | 4.3
94–95 | 0.168422 | 19,632 | 3,306 | 17,978 | 79,022 | 4.0
95–96 | 0.185437 | 16,325 | 3,027 | 14,811 | 61,044 | 3.7
96–97 | 0.203346 | 13,298 | 2,704 | 11,946 | 46,232 | 3.5
97–98 | 0.222042 | 10,594 | 2,352 | 9,418 | 34,287 | 3.2
98–99 | 0.241389 | 8,242 | 1,989 | 7,247 | 24,869 | 3.0
99–100 | 0.261232 | 6,252 | 1,633 | 5,435 | 17,622 | 2.8
100 and older | 1.000000 | 4,619 | 4,619 | 12,187 | 12,187 | 2.6
NOTES: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report. Hispanic people may be of any race.
SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 5

Life table for Hispanic males: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table05.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.005406 | 100,000 | 541 | 99,522 | 7,845,251 | 78.5
1–2 | 0.000430 | 99,459 | 43 | 99,438 | 7,745,729 | 77.9
2–3 | 0.000279 | 99,417 | 28 | 99,403 | 7,646,291 | 76.9
3–4 | 0.000195 | 99,389 | 19 | 99,379 | 7,546,888 | 75.9
4–5 | 0.000161 | 99,370 | 16 | 99,362 | 7,447,509 | 74.9
5–6 | 0.000139 | 99,354 | 14 | 99,347 | 7,348,147 | 74.0
6–7 | 0.000127 | 99,340 | 13 | 99,334 | 7,248,800 | 73.0
7–8 | 0.000115 | 99,327 | 11 | 99,321 | 7,149,467 | 72.0
8–9 | 0.000097 | 99,316 | 10 | 99,311 | 7,050,145 | 71.0
9–10 | 0.000074 | 99,306 | 7 | 99,302 | 6,950,835 | 70.0
10–11 | 0.000057 | 99,299 | 6 | 99,296 | 6,851,532 | 69.0
11–12 | 0.000062 | 99,293 | 6 | 99,290 | 6,752,236 | 68.0
12–13 | 0.000111 | 99,287 | 11 | 99,281 | 6,652,946 | 67.0
13–14 | 0.000212 | 99,276 | 21 | 99,265 | 6,553,665 | 66.0
14–15 | 0.000348 | 99,255 | 35 | 99,238 | 6,454,399 | 65.0
15–16 | 0.000498 | 99,220 | 49 | 99,196 | 6,355,162 | 64.1
16–17 | 0.000640 | 99,171 | 63 | 99,139 | 6,255,966 | 63.1
17–18 | 0.000770 | 99,107 | 76 | 99,069 | 6,156,827 | 62.1
18–19 | 0.000883 | 99,031 | 87 | 98,987 | 6,057,758 | 61.2
19–20 | 0.000987 | 98,944 | 98 | 98,895 | 5,958,770 | 60.2
20–21 | 0.001095 | 98,846 | 108 | 98,792 | 5,859,876 | 59.3
21–22 | 0.001214 | 98,738 | 120 | 98,678 | 5,761,084 | 58.3
22–23 | 0.001338 | 98,618 | 132 | 98,552 | 5,662,406 | 57.4
23–24 | 0.001465 | 98,486 | 144 | 98,414 | 5,563,854 | 56.5
24–25 | 0.001592 | 98,342 | 157 | 98,263 | 5,465,440 | 55.6
25–26 | 0.001720 | 98,185 | 169 | 98,101 | 5,367,176 | 54.7
26–27 | 0.001844 | 98,016 | 181 | 97,926 | 5,269,076 | 53.8
27–28 | 0.001952 | 97,836 | 191 | 97,740 | 5,171,150 | 52.9
28–29 | 0.002034 | 97,645 | 199 | 97,545 | 5,073,410 | 52.0
29–30 | 0.002096 | 97,446 | 204 | 97,344 | 4,975,865 | 51.1
30–31 | 0.002150 | 97,242 | 209 | 97,137 | 4,878,521 | 50.2
31–32 | 0.002202 | 97,033 | 214 | 96,926 | 4,781,384 | 49.3
32–33 | 0.002248 | 96,819 | 218 | 96,710 | 4,684,458 | 48.4
33–34 | 0.002291 | 96,601 | 221 | 96,491 | 4,587,748 | 47.5
34–35 | 0.002332 | 96,380 | 225 | 96,268 | 4,491,257 | 46.6
35–36 | 0.002370 | 96,155 | 228 | 96,041 | 4,394,990 | 45.7
36–37 | 0.002411 | 95,927 | 231 | 95,812 | 4,298,949 | 44.8
37–38 | 0.002466 | 95,696 | 236 | 95,578 | 4,203,137 | 43.9
38–39 | 0.002542 | 95,460 | 243 | 95,339 | 4,107,559 | 43.0
39–40 | 0.002632 | 95,217 | 251 | 95,092 | 4,012,220 | 42.1
40–41 | 0.002733 | 94,967 | 260 | 94,837 | 3,917,128 | 41.2
41–42 | 0.002834 | 94,707 | 268 | 94,573 | 3,822,291 | 40.4
42–43 | 0.002930 | 94,439 | 277 | 94,300 | 3,727,718 | 39.5
43–44 | 0.003016 | 94,162 | 284 | 94,020 | 3,633,418 | 38.6
44–45 | 0.003102 | 93,878 | 291 | 93,733 | 3,539,397 | 37.7
45–46 | 0.003199 | 93,587 | 299 | 93,437 | 3,445,665 | 36.8
46–47 | 0.003318 | 93,288 | 310 | 93,133 | 3,352,228 | 35.9
47–48 | 0.003462 | 92,978 | 322 | 92,817 | 3,259,095 | 35.1
48–49 | 0.003633 | 92,656 | 337 | 92,488 | 3,166,278 | 34.2
49–50 | 0.003832 | 92,320 | 354 | 92,143 | 3,073,790 | 33.3
50–51 | 0.004046 | 91,966 | 372 | 91,780 | 2,981,647 | 32.4
51–52 | 0.004287 | 91,594 | 393 | 91,397 | 2,889,868 | 31.6
52–53 | 0.004580 | 91,201 | 418 | 90,992 | 2,798,470 | 30.7
53–54 | 0.004942 | 90,783 | 449 | 90,559 | 2,707,478 | 29.8
54–55 | 0.005369 | 90,335 | 485 | 90,092 | 2,616,919 | 29.0
55–56 | 0.005835 | 89,850 | 524 | 89,587 | 2,526,827 | 28.1
56–57 | 0.006330 | 89,325 | 565 | 89,043 | 2,437,240 | 27.3
57–58 | 0.006872 | 88,760 | 610 | 88,455 | 2,348,197 | 26.5
58–59 | 0.007460 | 88,150 | 658 | 87,821 | 2,259,742 | 25.6
59–60 | 0.008092 | 87,492 | 708 | 87,138 | 2,171,921 | 24.8
60–61 | 0.008782 | 86,784 | 762 | 86,403 | 2,084,783 | 24.0
61–62 | 0.009511 | 86,022 | 818 | 85,613 | 1,998,380 | 23.2
62–63 | 0.010241 | 85,204 | 873 | 84,768 | 1,912,767 | 22.4
63–64 | 0.010956 | 84,331 | 924 | 83,869 | 1,827,999 | 21.7
64–65 | 0.011678 | 83,407 | 974 | 82,920 | 1,744,130 | 20.9
65–66 | 0.012445 | 82,433 | 1,026 | 81,920 | 1,661,209 | 20.2
66–67 | 0.013304 | 81,408 | 1,083 | 80,866 | 1,579,289 | 19.4
67–68 | 0.014278 | 80,325 | 1,147 | 79,751 | 1,498,423 | 18.7
68–69 | 0.015400 | 79,178 | 1,219 | 78,568 | 1,418,672 | 17.9
69–70 | 0.016665 | 77,958 | 1,299 | 77,309 | 1,340,104 | 17.2
70–71 | 0.018100 | 76,659 | 1,388 | 75,965 | 1,262,795 | 16.5
71–72 | 0.019670 | 75,272 | 1,481 | 74,531 | 1,186,830 | 15.8
72–73 | 0.021293 | 73,791 | 1,571 | 73,005 | 1,112,298 | 15.1
73–74 | 0.022893 | 72,220 | 1,653 | 71,393 | 1,039,293 | 14.4
74–75 | 0.024501 | 70,566 | 1,729 | 69,702 | 967,900 | 13.7
75–76 | 0.026160 | 68,837 | 1,801 | 67,937 | 898,198 | 13.0
76–77 | 0.028050 | 67,037 | 1,880 | 66,096 | 830,261 | 12.4
77–78 | 0.030806 | 65,156 | 2,007 | 64,153 | 764,165 | 11.7
78–79 | 0.033878 | 63,149 | 2,139 | 62,079 | 700,012 | 11.1
79–80 | 0.038018 | 61,010 | 2,319 | 59,850 | 637,933 | 10.5
80–81 | 0.041987 | 58,690 | 2,464 | 57,458 | 578,083 | 9.8
81–82 | 0.047365 | 56,226 | 2,663 | 54,894 | 520,625 | 9.3
82–83 | 0.053001 | 53,563 | 2,839 | 52,143 | 465,730 | 8.7
83–84 | 0.058557 | 50,724 | 2,970 | 49,239 | 413,587 | 8.2
84–85 | 0.064829 | 47,754 | 3,096 | 46,206 | 364,348 | 7.6
85–86 | 0.071909 | 44,658 | 3,211 | 43,052 | 318,142 | 7.1
86–87 | 0.079707 | 41,447 | 3,304 | 39,795 | 275,090 | 6.6
87–88 | 0.089831 | 38,143 | 3,426 | 36,430 | 235,295 | 6.2
88–89 | 0.100988 | 34,717 | 3,506 | 32,964 | 198,866 | 5.7
89–90 | 0.113216 | 31,211 | 3,534 | 29,444 | 165,902 | 5.3
90–91 | 0.126540 | 27,677 | 3,502 | 25,926 | 136,458 | 4.9
91–92 | 0.140968 | 24,175 | 3,408 | 22,471 | 110,532 | 4.6
92–93 | 0.156482 | 20,767 | 3,250 | 19,142 | 88,061 | 4.2
93–94 | 0.173041 | 17,517 | 3,031 | 16,002 | 68,919 | 3.9
94–95 | 0.190576 | 14,486 | 2,761 | 13,106 | 52,918 | 3.7
95–96 | 0.208989 | 11,725 | 2,450 | 10,500 | 39,812 | 3.4
96–97 | 0.228153 | 9,275 | 2,116 | 8,217 | 29,312 | 3.2
97–98 | 0.247915 | 7,159 | 1,775 | 6,271 | 21,095 | 2.9
98–99 | 0.268101 | 5,384 | 1,443 | 4,662 | 14,823 | 2.8
99–100 | 0.288519 | 3,941 | 1,137 | 3,372 | 10,161 | 2.6
100 and older | 1.000000 | 2,804 | 2,804 | 6,789 | 6,789 | 2.4

NOTES: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report. Hispanic people may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 6

Life table for Hispanic females: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table06.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.004639 | 100,000 | 464 | 99,594 | 8,396,844 | 84.0
1–2 | 0.000302 | 99,536 | 30 | 99,521 | 8,297,251 | 83.4
2–3 | 0.000174 | 99,506 | 17 | 99,497 | 8,197,730 | 82.4
3–4 | 0.000148 | 99,489 | 15 | 99,481 | 8,098,233 | 81.4
4–5 | 0.000106 | 99,474 | 11 | 99,469 | 7,998,751 | 80.4
5–6 | 0.000101 | 99,463 | 10 | 99,458 | 7,899,283 | 79.4
6–7 | 0.000093 | 99,453 | 9 | 99,449 | 7,799,824 | 78.4
7–8 | 0.000089 | 99,444 | 9 | 99,440 | 7,700,375 | 77.4
8–9 | 0.000085 | 99,435 | 8 | 99,431 | 7,600,936 | 76.4
9–10 | 0.000083 | 99,427 | 8 | 99,423 | 7,501,505 | 75.4
10–11 | 0.000085 | 99,419 | 8 | 99,414 | 7,402,082 | 74.5
11–12 | 0.000093 | 99,410 | 9 | 99,406 | 7,302,668 | 73.5
12–13 | 0.000113 | 99,401 | 11 | 99,395 | 7,203,262 | 72.5
13–14 | 0.000147 | 99,390 | 15 | 99,382 | 7,103,867 | 71.5
14–15 | 0.000190 | 99,375 | 19 | 99,366 | 7,004,485 | 70.5
15–16 | 0.000236 | 99,356 | 23 | 99,344 | 6,905,119 | 69.5
16–17 | 0.000280 | 99,333 | 28 | 99,319 | 6,805,775 | 68.5
17–18 | 0.000319 | 99,305 | 32 | 99,289 | 6,706,456 | 67.5
18–19 | 0.000352 | 99,273 | 35 | 99,256 | 6,607,167 | 66.6
19–20 | 0.000381 | 99,238 | 38 | 99,219 | 6,507,911 | 65.6
20–21 | 0.000413 | 99,200 | 41 | 99,180 | 6,408,692 | 64.6
21–22 | 0.000446 | 99,160 | 44 | 99,137 | 6,309,512 | 63.6
22–23 | 0.000474 | 99,115 | 47 | 99,092 | 6,210,374 | 62.7
23–24 | 0.000492 | 99,068 | 49 | 99,044 | 6,111,282 | 61.7
24–25 | 0.000505 | 99,020 | 50 | 98,995 | 6,012,238 | 60.7
25–26 | 0.000514 | 98,970 | 51 | 98,944 | 5,913,244 | 59.7
26–27 | 0.000526 | 98,919 | 52 | 98,893 | 5,814,300 | 58.8
27–28 | 0.000546 | 98,867 | 54 | 98,840 | 5,715,407 | 57.8
28–29 | 0.000578 | 98,813 | 57 | 98,784 | 5,616,567 | 56.8
29–30 | 0.000618 | 98,756 | 61 | 98,725 | 5,517,783 | 55.9
30–31 | 0.000661 | 98,695 | 65 | 98,662 | 5,419,058 | 54.9
31–32 | 0.000702 | 98,629 | 69 | 98,595 | 5,320,396 | 53.9
32–33 | 0.000740 | 98,560 | 73 | 98,524 | 5,221,802 | 53.0
33–34 | 0.000774 | 98,487 | 76 | 98,449 | 5,123,278 | 52.0
34–35 | 0.000806 | 98,411 | 79 | 98,371 | 5,024,829 | 51.1
35–36 | 0.000841 | 98,332 | 83 | 98,290 | 4,926,458 | 50.1
36–37 | 0.000882 | 98,249 | 87 | 98,206 | 4,828,167 | 49.1
37–38 | 0.000926 | 98,162 | 91 | 98,117 | 4,729,962 | 48.2
38–39 | 0.000973 | 98,072 | 95 | 98,024 | 4,631,845 | 47.2
39–40 | 0.001022 | 97,976 | 100 | 97,926 | 4,533,821 | 46.3
40–41 | 0.001073 | 97,876 | 105 | 97,823 | 4,435,895 | 45.3
41–42 | 0.001130 | 97,771 | 111 | 97,716 | 4,338,071 | 44.4
42–43 | 0.001199 | 97,660 | 117 | 97,602 | 4,240,356 | 43.4
43–44 | 0.001284 | 97,543 | 125 | 97,481 | 4,142,754 | 42.5
44–45 | 0.001385 | 97,418 | 135 | 97,351 | 4,045,273 | 41.5
45–46 | 0.001498 | 97,283 | 146 | 97,210 | 3,947,923 | 40.6
46–47 | 0.001619 | 97,137 | 157 | 97,059 | 3,850,712 | 39.6
47–48 | 0.001747 | 96,980 | 169 | 96,895 | 3,753,654 | 38.7
48–49 | 0.001879 | 96,811 | 182 | 96,720 | 3,656,758 | 37.8
49–50 | 0.002016 | 96,629 | 195 | 96,531 | 3,560,039 | 36.8
50–51 | 0.002166 | 96,434 | 209 | 96,329 | 3,463,507 | 35.9
51–52 | 0.002330 | 96,225 | 224 | 96,113 | 3,367,178 | 35.0
52–53 | 0.002505 | 96,001 | 240 | 95,880 | 3,271,065 | 34.1
53–54 | 0.002691 | 95,760 | 258 | 95,631 | 3,175,185 | 33.2
54–55 | 0.002896 | 95,503 | 277 | 95,364 | 3,079,553 | 32.2
55–56 | 0.003110 | 95,226 | 296 | 95,078 | 2,984,189 | 31.3
56–57 | 0.003350 | 94,930 | 318 | 94,771 | 2,889,111 | 30.4
57–58 | 0.003647 | 94,612 | 345 | 94,439 | 2,794,340 | 29.5
58–59 | 0.004017 | 94,267 | 379 | 94,077 | 2,699,901 | 28.6
59–60 | 0.004446 | 93,888 | 417 | 93,679 | 2,605,824 | 27.8
60–61 | 0.004927 | 93,471 | 461 | 93,240 | 2,512,145 | 26.9
61–62 | 0.005424 | 93,010 | 504 | 92,758 | 2,418,904 | 26.0
62–63 | 0.005895 | 92,506 | 545 | 92,233 | 2,326,147 | 25.1
63–64 | 0.006316 | 91,960 | 581 | 91,670 | 2,233,914 | 24.3
64–65 | 0.006711 | 91,379 | 613 | 91,073 | 2,142,244 | 23.4
65–66 | 0.007123 | 90,766 | 647 | 90,443 | 2,051,171 | 22.6
66–67 | 0.007609 | 90,120 | 686 | 89,777 | 1,960,728 | 21.8
67–68 | 0.008210 | 89,434 | 734 | 89,067 | 1,870,952 | 20.9
68–69 | 0.008973 | 88,700 | 796 | 88,302 | 1,781,885 | 20.1
69–70 | 0.009895 | 87,904 | 870 | 87,469 | 1,693,583 | 19.3
70–71 | 0.010950 | 87,034 | 953 | 86,557 | 1,606,114 | 18.5
71–72 | 0.012112 | 86,081 | 1,043 | 85,560 | 1,519,557 | 17.7
72–73 | 0.013392 | 85,038 | 1,139 | 84,469 | 1,433,997 | 16.9
73–74 | 0.014777 | 83,900 | 1,240 | 83,280 | 1,349,528 | 16.1
74–75 | 0.016287 | 82,660 | 1,346 | 81,987 | 1,266,249 | 15.3
75–76 | 0.017961 | 81,314 | 1,461 | 80,583 | 1,184,262 | 14.6
76–77 | 0.019810 | 79,853 | 1,582 | 79,062 | 1,103,679 | 13.8
77–78 | 0.022176 | 78,271 | 1,736 | 77,403 | 1,024,617 | 13.1
78–79 | 0.024663 | 76,535 | 1,888 | 75,592 | 947,213 | 12.4
79–80 | 0.027832 | 74,648 | 2,078 | 73,609 | 871,622 | 11.7
80–81 | 0.031135 | 72,570 | 2,259 | 71,440 | 798,013 | 11.0
81–82 | 0.035361 | 70,311 | 2,486 | 69,068 | 726,572 | 10.3
82–83 | 0.039863 | 67,824 | 2,704 | 66,473 | 657,505 | 9.7
83–84 | 0.044895 | 65,121 | 2,924 | 63,659 | 591,032 | 9.1
84–85 | 0.050770 | 62,197 | 3,158 | 60,618 | 527,373 | 8.5
85–86 | 0.056207 | 59,039 | 3,318 | 57,380 | 466,755 | 7.9
86–87 | 0.064229 | 55,721 | 3,579 | 53,932 | 409,375 | 7.3
87–88 | 0.073245 | 52,142 | 3,819 | 50,233 | 355,443 | 6.8
88–89 | 0.083335 | 48,323 | 4,027 | 46,309 | 305,211 | 6.3
89–90 | 0.094572 | 44,296 | 4,189 | 42,201 | 258,901 | 5.8
90–91 | 0.107021 | 40,107 | 4,292 | 37,961 | 216,700 | 5.4
91–92 | 0.120730 | 35,815 | 4,324 | 33,653 | 178,739 | 5.0
92–93 | 0.135731 | 31,491 | 4,274 | 29,354 | 145,086 | 4.6
93–94 | 0.152027 | 27,216 | 4,138 | 25,148 | 115,733 | 4.3
94–95 | 0.169597 | 23,079 | 3,914 | 21,122 | 90,585 | 3.9
95–96 | 0.188385 | 19,165 | 3,610 | 17,360 | 69,463 | 3.6
96–97 | 0.208298 | 15,554 | 3,240 | 13,934 | 52,104 | 3.3
97–98 | 0.229209 | 12,314 | 2,823 | 10,903 | 38,170 | 3.1
98–99 | 0.250956 | 9,492 | 2,382 | 8,301 | 27,266 | 2.9
99–100 | 0.273346 | 7,110 | 1,943 | 6,138 | 18,966 | 2.7
100 and older | 1.000000 | 5,166 | 5,166 | 12,828 | 12,828 | 2.5

NOTES: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report. Hispanic people may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 7

Life table for the American Indian and Alaska Native, non-Hispanic population: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table07.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.009124 | 100,000 | 912 | 99,252 | 7,005,082 | 70.1
1–2 | 0.001154 | 99,088 | 114 | 99,030 | 6,905,830 | 69.7
2–3 | 0.000528 | 98,973 | 52 | 98,947 | 6,806,799 | 68.8
3–4 | 0.000462 | 98,921 | 46 | 98,898 | 6,707,852 | 67.8
4–5 | 0.000362 | 98,875 | 36 | 98,857 | 6,608,954 | 66.8
5–6 | 0.000248 | 98,839 | 25 | 98,827 | 6,510,097 | 65.9
6–7 | 0.000212 | 98,815 | 21 | 98,804 | 6,411,269 | 64.9
7–8 | 0.000191 | 98,794 | 19 | 98,785 | 6,312,465 | 63.9
8–9 | 0.000175 | 98,775 | 17 | 98,766 | 6,213,681 | 62.9
9–10 | 0.000165 | 98,758 | 16 | 98,750 | 6,114,914 | 61.9
10–11 | 0.000171 | 98,742 | 17 | 98,733 | 6,016,164 | 60.9
11–12 | 0.000214 | 98,725 | 21 | 98,714 | 5,917,431 | 59.9
12–13 | 0.000315 | 98,703 | 31 | 98,688 | 5,818,717 | 59.0
13–14 | 0.000482 | 98,672 | 48 | 98,649 | 5,720,030 | 58.0
14–15 | 0.000696 | 98,625 | 69 | 98,591 | 5,621,381 | 57.0
15–16 | 0.000935 | 98,556 | 92 | 98,510 | 5,522,790 | 56.0
16–17 | 0.001170 | 98,464 | 115 | 98,406 | 5,424,280 | 55.1
17–18 | 0.001387 | 98,349 | 136 | 98,281 | 5,325,874 | 54.2
18–19 | 0.001575 | 98,213 | 155 | 98,135 | 5,227,593 | 53.2
19–20 | 0.001750 | 98,058 | 172 | 97,972 | 5,129,458 | 52.3
20–21 | 0.001941 | 97,886 | 190 | 97,791 | 5,031,486 | 51.4
21–22 | 0.002160 | 97,696 | 211 | 97,591 | 4,933,695 | 50.5
22–23 | 0.002393 | 97,485 | 233 | 97,369 | 4,836,104 | 49.6
23–24 | 0.002636 | 97,252 | 256 | 97,124 | 4,738,735 | 48.7
24–25 | 0.002894 | 96,996 | 281 | 96,855 | 4,641,611 | 47.9
25–26 | 0.003141 | 96,715 | 304 | 96,563 | 4,544,756 | 47.0
26–27 | 0.003407 | 96,411 | 328 | 96,247 | 4,448,193 | 46.1
27–28 | 0.003738 | 96,083 | 359 | 95,903 | 4,351,946 | 45.3
28–29 | 0.004138 | 95,723 | 396 | 95,525 | 4,256,043 | 44.5
29–30 | 0.004565 | 95,327 | 435 | 95,110 | 4,160,518 | 43.6
30–31 | 0.004988 | 94,892 | 473 | 94,656 | 4,065,408 | 42.8
31–32 | 0.005366 | 94,419 | 507 | 94,165 | 3,970,753 | 42.1
32–33 | 0.005687 | 93,912 | 534 | 93,645 | 3,876,587 | 41.3
33–34 | 0.005953 | 93,378 | 556 | 93,100 | 3,782,942 | 40.5
34–35 | 0.006192 | 92,822 | 575 | 92,535 | 3,689,842 | 39.8
35–36 | 0.006449 | 92,247 | 595 | 91,950 | 3,597,307 | 39.0
36–37 | 0.006732 | 91,652 | 617 | 91,344 | 3,505,357 | 38.2
37–38 | 0.006998 | 91,035 | 637 | 90,717 | 3,414,013 | 37.5
38–39 | 0.007226 | 90,398 | 653 | 90,072 | 3,323,296 | 36.8
39–40 | 0.007424 | 89,745 | 666 | 89,412 | 3,233,225 | 36.0
40–41 | 0.007606 | 89,079 | 678 | 88,740 | 3,143,813 | 35.3
41–42 | 0.007820 | 88,401 | 691 | 88,056 | 3,055,072 | 34.6
42–43 | 0.008108 | 87,710 | 711 | 87,355 | 2,967,017 | 33.8
43–44 | 0.008509 | 86,999 | 740 | 86,629 | 2,879,662 | 33.1
44–45 | 0.009014 | 86,259 | 777 | 85,870 | 2,793,033 | 32.4
45–46 | 0.009584 | 85,481 | 819 | 85,072 | 2,707,163 | 31.7
46–47 | 0.010171 | 84,662 | 861 | 84,231 | 2,622,092 | 31.0
47–48 | 0.010752 | 83,801 | 901 | 83,350 | 2,537,861 | 30.3
48–49 | 0.011278 | 82,900 | 935 | 82,432 | 2,454,510 | 29.6
49–50 | 0.011749 | 81,965 | 963 | 81,483 | 2,372,078 | 28.9
50–51 | 0.012217 | 81,002 | 990 | 80,507 | 2,290,595 | 28.3
51–52 | 0.012706 | 80,012 | 1,017 | 79,504 | 2,210,088 | 27.6
52–53 | 0.013188 | 78,996 | 1,042 | 78,475 | 2,130,584 | 27.0
53–54 | 0.013672 | 77,954 | 1,066 | 77,421 | 2,052,109 | 26.3
54–55 | 0.014173 | 76,888 | 1,090 | 76,343 | 1,974,688 | 25.7
55–56 | 0.014652 | 75,798 | 1,111 | 75,243 | 1,898,345 | 25.0
56–57 | 0.015155 | 74,688 | 1,132 | 74,122 | 1,823,102 | 24.4
57–58 | 0.015773 | 73,556 | 1,160 | 72,976 | 1,748,980 | 23.8
58–59 | 0.016528 | 72,396 | 1,197 | 71,797 | 1,676,004 | 23.2
59–60 | 0.017359 | 71,199 | 1,236 | 70,581 | 1,604,207 | 22.5
60–61 | 0.018205 | 69,963 | 1,274 | 69,326 | 1,533,626 | 21.9
61–62 | 0.019004 | 68,689 | 1,305 | 68,037 | 1,464,300 | 21.3
62–63 | 0.019742 | 67,384 | 1,330 | 66,719 | 1,396,263 | 20.7
63–64 | 0.020420 | 66,054 | 1,349 | 65,379 | 1,329,544 | 20.1
64–65 | 0.021085 | 64,705 | 1,364 | 64,023 | 1,264,165 | 19.5
65–66 | 0.021773 | 63,341 | 1,379 | 62,651 | 1,200,142 | 18.9
66–67 | 0.022533 | 61,962 | 1,396 | 61,263 | 1,137,491 | 18.4
67–68 | 0.023408 | 60,565 | 1,418 | 59,856 | 1,076,227 | 17.8
68–69 | 0.024437 | 59,148 | 1,445 | 58,425 | 1,016,371 | 17.2
69–70 | 0.025613 | 57,702 | 1,478 | 56,963 | 957,946 | 16.6
70–71 | 0.026956 | 56,224 | 1,516 | 55,467 | 900,983 | 16.0
71–72 | 0.028417 | 54,709 | 1,555 | 53,931 | 845,516 | 15.5
72–73 | 0.029908 | 53,154 | 1,590 | 52,359 | 791,585 | 14.9
73–74 | 0.031359 | 51,564 | 1,617 | 50,756 | 739,225 | 14.3
74–75 | 0.032817 | 49,947 | 1,639 | 49,128 | 688,469 | 13.8
75–76 | 0.034324 | 48,308 | 1,658 | 47,479 | 639,342 | 13.2
76–77 | 0.036094 | 46,650 | 1,684 | 45,808 | 591,862 | 12.7
77–78 | 0.038392 | 44,966 | 1,726 | 44,103 | 546,054 | 12.1
78–79 | 0.041491 | 43,240 | 1,794 | 42,343 | 501,951 | 11.6
79–80 | 0.045421 | 41,446 | 1,882 | 40,505 | 459,608 | 11.1
80–81 | 0.050100 | 39,563 | 1,982 | 38,572 | 419,104 | 10.6
81–82 | 0.054829 | 37,581 | 2,061 | 36,551 | 380,531 | 10.1
82–83 | 0.059223 | 35,521 | 2,104 | 34,469 | 343,980 | 9.7
83–84 | 0.062985 | 33,417 | 2,105 | 32,365 | 309,511 | 9.3
84–85 | 0.066574 | 31,312 | 2,085 | 30,270 | 277,147 | 8.9
85–86 | 0.069756 | 29,228 | 2,039 | 28,208 | 246,877 | 8.4
86–87 | 0.075225 | 27,189 | 2,045 | 26,166 | 218,668 | 8.0
87–88 | 0.081043 | 25,144 | 2,038 | 24,125 | 192,502 | 7.7
88–89 | 0.087217 | 23,106 | 2,015 | 22,098 | 168,377 | 7.3
89–90 | 0.093752 | 21,091 | 1,977 | 20,102 | 146,279 | 6.9
90–91 | 0.100649 | 19,113 | 1,924 | 18,152 | 126,177 | 6.6
91–92 | 0.107905 | 17,190 | 1,855 | 16,262 | 108,025 | 6.3
92–93 | 0.115512 | 15,335 | 1,771 | 14,449 | 91,763 | 6.0
93–94 | 0.123457 | 13,563 | 1,675 | 12,726 | 77,314 | 5.7
94–95 | 0.131721 | 11,889 | 1,566 | 11,106 | 64,588 | 5.4
95–96 | 0.140281 | 10,323 | 1,448 | 9,599 | 53,482 | 5.2
96–97 | 0.149105 | 8,875 | 1,323 | 8,213 | 43,883 | 4.9
97–98 | 0.158155 | 7,552 | 1,194 | 6,954 | 35,670 | 4.7
98–99 | 0.167387 | 6,357 | 1,064 | 5,825 | 28,715 | 4.5
99–100 | 0.176753 | 5,293 | 936 | 4,825 | 22,890 | 4.3
100 and older | 1.000000 | 4,358 | 4,358 | 18,065 | 18,065 | 4.1

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 8

Life table for American Indian and Alaska Native, non-Hispanic males: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table08.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.010226 | 100,000 | 1,023 | 99,186 | 6,672,162 | 66.7
1–2 | 0.001579 | 98,977 | 156 | 98,899 | 6,572,976 | 66.4
2–3 | 0.000443 | 98,821 | 44 | 98,799 | 6,474,077 | 65.5
3–4 | 0.000423 | 98,777 | 42 | 98,756 | 6,375,278 | 64.5
4–5 | 0.000405 | 98,736 | 40 | 98,716 | 6,276,521 | 63.6
5–6 | 0.000195 | 98,696 | 19 | 98,686 | 6,177,805 | 62.6
6–7 | 0.000157 | 98,676 | 16 | 98,669 | 6,079,119 | 61.6
7–8 | 0.000144 | 98,661 | 14 | 98,654 | 5,980,451 | 60.6
8–9 | 0.000147 | 98,647 | 15 | 98,639 | 5,881,797 | 59.6
9–10 | 0.000166 | 98,632 | 16 | 98,624 | 5,783,158 | 58.6
10–11 | 0.000208 | 98,616 | 21 | 98,605 | 5,684,534 | 57.6
11–12 | 0.000286 | 98,595 | 28 | 98,581 | 5,585,928 | 56.7
12–13 | 0.000414 | 98,567 | 41 | 98,547 | 5,487,347 | 55.7
13–14 | 0.000597 | 98,526 | 59 | 98,497 | 5,388,801 | 54.7
14–15 | 0.000821 | 98,467 | 81 | 98,427 | 5,290,304 | 53.7
15–16 | 0.001072 | 98,387 | 105 | 98,334 | 5,191,877 | 52.8
16–17 | 0.001328 | 98,281 | 130 | 98,216 | 5,093,543 | 51.8
17–18 | 0.001575 | 98,151 | 155 | 98,073 | 4,995,327 | 50.9
18–19 | 0.001806 | 97,996 | 177 | 97,908 | 4,897,254 | 50.0
19–20 | 0.002035 | 97,819 | 199 | 97,720 | 4,799,346 | 49.1
20–21 | 0.002290 | 97,620 | 224 | 97,508 | 4,701,627 | 48.2
21–22 | 0.002578 | 97,396 | 251 | 97,271 | 4,604,119 | 47.3
22–23 | 0.002885 | 97,145 | 280 | 97,005 | 4,506,848 | 46.4
23–24 | 0.003211 | 96,865 | 311 | 96,710 | 4,409,842 | 45.5
24–25 | 0.003556 | 96,554 | 343 | 96,382 | 4,313,133 | 44.7
25–26 | 0.003892 | 96,211 | 374 | 96,024 | 4,216,750 | 43.8
26–27 | 0.004254 | 95,836 | 408 | 95,632 | 4,120,727 | 43.0
27–28 | 0.004706 | 95,429 | 449 | 95,204 | 4,025,094 | 42.2
28–29 | 0.005253 | 94,979 | 499 | 94,730 | 3,929,890 | 41.4
29–30 | 0.005833 | 94,481 | 551 | 94,205 | 3,835,160 | 40.6
30–31 | 0.006399 | 93,929 | 601 | 93,629 | 3,740,955 | 39.8
31–32 | 0.006901 | 93,328 | 644 | 93,006 | 3,647,326 | 39.1
32–33 | 0.007331 | 92,684 | 680 | 92,345 | 3,554,320 | 38.3
33–34 | 0.007698 | 92,005 | 708 | 91,651 | 3,461,975 | 37.6
34–35 | 0.008032 | 91,297 | 733 | 90,930 | 3,370,325 | 36.9
35–36 | 0.008410 | 90,563 | 762 | 90,182 | 3,279,395 | 36.2
36–37 | 0.008809 | 89,802 | 791 | 89,406 | 3,189,212 | 35.5
37–38 | 0.009120 | 89,011 | 812 | 88,605 | 3,099,806 | 34.8
38–39 | 0.009281 | 88,199 | 819 | 87,789 | 3,011,201 | 34.1
39–40 | 0.009337 | 87,380 | 816 | 86,972 | 2,923,412 | 33.5
40–41 | 0.009327 | 86,564 | 807 | 86,161 | 2,836,440 | 32.8
41–42 | 0.009388 | 85,757 | 805 | 85,354 | 2,750,279 | 32.1
42–43 | 0.009652 | 84,952 | 820 | 84,542 | 2,664,925 | 31.4
43–44 | 0.010225 | 84,132 | 860 | 83,702 | 2,580,383 | 30.7
44–45 | 0.011054 | 83,272 | 921 | 82,811 | 2,496,681 | 30.0
45–46 | 0.012031 | 82,351 | 991 | 81,856 | 2,413,870 | 29.3
46–47 | 0.012992 | 81,360 | 1,057 | 80,832 | 2,332,014 | 28.7
47–48 | 0.013844 | 80,303 | 1,112 | 79,747 | 2,251,183 | 28.0
48–49 | 0.014459 | 79,192 | 1,145 | 78,619 | 2,171,435 | 27.4
49–50 | 0.014882 | 78,047 | 1,162 | 77,466 | 2,092,816 | 26.8
50–51 | 0.015280 | 76,885 | 1,175 | 76,298 | 2,015,350 | 26.2
51–52 | 0.015743 | 75,710 | 1,192 | 75,114 | 1,939,053 | 25.6
52–53 | 0.016216 | 74,518 | 1,208 | 73,914 | 1,863,938 | 25.0
53–54 | 0.016729 | 73,310 | 1,226 | 72,697 | 1,790,024 | 24.4
54–55 | 0.017300 | 72,083 | 1,247 | 71,460 | 1,717,328 | 23.8
55–56 | 0.017837 | 70,836 | 1,264 | 70,205 | 1,645,868 | 23.2
56–57 | 0.018415 | 69,573 | 1,281 | 68,932 | 1,575,663 | 22.6
57–58 | 0.019215 | 68,292 | 1,312 | 67,636 | 1,506,731 | 22.1
58–59 | 0.020286 | 66,979 | 1,359 | 66,300 | 1,439,095 | 21.5
59–60 | 0.021519 | 65,621 | 1,412 | 64,915 | 1,372,795 | 20.9
60–61 | 0.022782 | 64,209 | 1,463 | 63,477 | 1,307,880 | 20.4
61–62 | 0.023960 | 62,746 | 1,503 | 61,994 | 1,244,403 | 19.8
62–63 | 0.025042 | 61,242 | 1,534 | 60,476 | 1,182,409 | 19.3
63–64 | 0.026021 | 59,709 | 1,554 | 58,932 | 1,121,934 | 18.8
64–65 | 0.026958 | 58,155 | 1,568 | 57,371 | 1,063,002 | 18.3
65–66 | 0.027936 | 56,587 | 1,581 | 55,797 | 1,005,630 | 17.8
66–67 | 0.028984 | 55,007 | 1,594 | 54,209 | 949,833 | 17.3
67–68 | 0.030067 | 53,412 | 1,606 | 52,609 | 895,624 | 16.8
68–69 | 0.031176 | 51,806 | 1,615 | 50,999 | 843,015 | 16.3
69–70 | 0.032313 | 50,191 | 1,622 | 49,380 | 792,016 | 15.8
70–71 | 0.033554 | 48,569 | 1,630 | 47,754 | 742,636 | 15.3
71–72 | 0.034886 | 46,940 | 1,638 | 46,121 | 694,881 | 14.8
72–73 | 0.036188 | 45,302 | 1,639 | 44,482 | 648,761 | 14.3
73–74 | 0.037392 | 43,663 | 1,633 | 42,846 | 604,278 | 13.8
74–75 | 0.038547 | 42,030 | 1,620 | 41,220 | 561,432 | 13.4
75–76 | 0.039653 | 40,410 | 1,602 | 39,609 | 520,212 | 12.9
76–77 | 0.040943 | 38,808 | 1,589 | 38,013 | 480,603 | 12.4
77–78 | 0.042769 | 37,219 | 1,592 | 36,423 | 442,590 | 11.9
78–79 | 0.045473 | 35,627 | 1,620 | 34,817 | 406,167 | 11.4
79–80 | 0.049085 | 34,007 | 1,669 | 33,172 | 371,351 | 10.9
80–81 | 0.053625 | 32,338 | 1,734 | 31,471 | 338,178 | 10.5
81–82 | 0.058275 | 30,603 | 1,783 | 29,712 | 306,708 | 10.0
82–83 | 0.062620 | 28,820 | 1,805 | 27,918 | 276,996 | 9.6
83–84 | 0.066226 | 27,015 | 1,789 | 26,121 | 249,079 | 9.2
84–85 | 0.069613 | 25,226 | 1,756 | 24,348 | 222,958 | 8.8
85–86 | 0.073230 | 23,470 | 1,719 | 22,611 | 198,610 | 8.5
86–87 | 0.077639 | 21,751 | 1,689 | 20,907 | 175,999 | 8.1
87–88 | 0.083119 | 20,063 | 1,668 | 19,229 | 155,092 | 7.7
88–89 | 0.088891 | 18,395 | 1,635 | 17,578 | 135,863 | 7.4
89–90 | 0.094954 | 16,760 | 1,591 | 15,964 | 118,285 | 7.1
90–91 | 0.101303 | 15,169 | 1,537 | 14,400 | 102,321 | 6.7
91–92 | 0.107928 | 13,632 | 1,471 | 12,896 | 87,921 | 6.4
92–93 | 0.114815 | 12,161 | 1,396 | 11,463 | 75,025 | 6.2
93–94 | 0.121948 | 10,764 | 1,313 | 10,108 | 63,562 | 5.9
94–95 | 0.129301 | 9,452 | 1,222 | 8,841 | 53,454 | 5.7
95–96 | 0.136847 | 8,230 | 1,126 | 7,667 | 44,613 | 5.4
96–97 | 0.144550 | 7,103 | 1,027 | 6,590 | 36,947 | 5.2
97–98 | 0.152371 | 6,077 | 926 | 5,614 | 30,357 | 5.0
98–99 | 0.160267 | 5,151 | 825 | 4,738 | 24,743 | 4.8
99–100 | 0.168189 | 4,325 | 727 | 3,961 | 20,005 | 4.6
100 and older | 1.000000 | 3,598 | 3,598 | 16,044 | 16,044 | 4.5

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 9

Life table for American Indian and Alaska Native, non-Hispanic females: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table09.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.007900 | 100,000 | 790 | 99,330 | 7,352,711 | 73.5
1–2 | 0.000727 | 99,210 | 72 | 99,174 | 7,253,381 | 73.1
2–3 | 0.000607 | 99,138 | 60 | 99,108 | 7,154,207 | 72.2
3–4 | 0.000497 | 99,078 | 49 | 99,053 | 7,055,099 | 71.2
4–5 | 0.000317 | 99,029 | 31 | 99,013 | 6,956,046 | 70.2
5–6 | 0.000297 | 98,997 | 29 | 98,983 | 6,857,033 | 69.3
6–7 | 0.000265 | 98,968 | 26 | 98,955 | 6,758,050 | 68.3
7–8 | 0.000236 | 98,942 | 23 | 98,930 | 6,659,096 | 67.3
8–9 | 0.000200 | 98,918 | 20 | 98,908 | 6,560,166 | 66.3
9–10 | 0.000159 | 98,898 | 16 | 98,891 | 6,461,257 | 65.3
10–11 | 0.000129 | 98,883 | 13 | 98,876 | 6,362,367 | 64.3
11–12 | 0.000135 | 98,870 | 13 | 98,863 | 6,263,491 | 63.4
12–13 | 0.000210 | 98,857 | 21 | 98,846 | 6,164,627 | 62.4
13–14 | 0.000368 | 98,836 | 36 | 98,818 | 6,065,781 | 61.4
14–15 | 0.000579 | 98,799 | 57 | 98,771 | 5,966,964 | 60.4
15–16 | 0.000814 | 98,742 | 80 | 98,702 | 5,868,193 | 59.4
16–17 | 0.001036 | 98,662 | 102 | 98,611 | 5,769,491 | 58.5
17–18 | 0.001227 | 98,560 | 121 | 98,499 | 5,670,880 | 57.5
18–19 | 0.001377 | 98,439 | 136 | 98,371 | 5,572,381 | 56.6
19–20 | 0.001500 | 98,303 | 147 | 98,229 | 5,474,010 | 55.7
20–21 | 0.001631 | 98,156 | 160 | 98,076 | 5,375,781 | 54.8
21–22 | 0.001782 | 97,996 | 175 | 97,908 | 5,277,705 | 53.9
22–23 | 0.001935 | 97,821 | 189 | 97,726 | 5,179,797 | 53.0
23–24 | 0.002086 | 97,632 | 204 | 97,530 | 5,082,071 | 52.1
24–25 | 0.002239 | 97,428 | 218 | 97,319 | 4,984,541 | 51.2
25–26 | 0.002381 | 97,210 | 231 | 97,094 | 4,887,222 | 50.3
26–27 | 0.002536 | 96,978 | 246 | 96,855 | 4,790,128 | 49.4
27–28 | 0.002734 | 96,732 | 265 | 96,600 | 4,693,273 | 48.5
28–29 | 0.002983 | 96,468 | 288 | 96,324 | 4,596,672 | 47.6
29–30 | 0.003255 | 96,180 | 313 | 96,024 | 4,500,348 | 46.8
30–31 | 0.003532 | 95,867 | 339 | 95,698 | 4,404,325 | 45.9
31–32 | 0.003784 | 95,528 | 361 | 95,348 | 4,308,627 | 45.1
32–33 | 0.003994 | 95,167 | 380 | 94,977 | 4,213,279 | 44.3
33–34 | 0.004162 | 94,787 | 394 | 94,590 | 4,118,302 | 43.4
34–35 | 0.004310 | 94,392 | 407 | 94,189 | 4,023,712 | 42.6
35–36 | 0.004456 | 93,986 | 419 | 93,776 | 3,929,523 | 41.8
36–37 | 0.004631 | 93,567 | 433 | 93,350 | 3,835,747 | 41.0
37–38 | 0.004863 | 93,133 | 453 | 92,907 | 3,742,397 | 40.2
38–39 | 0.005164 | 92,681 | 479 | 92,441 | 3,649,490 | 39.4
39–40 | 0.005508 | 92,202 | 508 | 91,948 | 3,557,049 | 38.6
40–41 | 0.005887 | 91,694 | 540 | 91,424 | 3,465,101 | 37.8
41–42 | 0.006258 | 91,154 | 570 | 90,869 | 3,373,677 | 37.0
42–43 | 0.006573 | 90,584 | 595 | 90,286 | 3,282,808 | 36.2
43–44 | 0.006808 | 89,988 | 613 | 89,682 | 3,192,522 | 35.5
44–45 | 0.006998 | 89,376 | 625 | 89,063 | 3,102,839 | 34.7
45–46 | 0.007177 | 88,750 | 637 | 88,432 | 3,013,776 | 34.0
46–47 | 0.007409 | 88,113 | 653 | 87,787 | 2,925,345 | 33.2
47–48 | 0.007732 | 87,460 | 676 | 87,122 | 2,837,558 | 32.4
48–49 | 0.008172 | 86,784 | 709 | 86,430 | 2,750,435 | 31.7
49–50 | 0.008688 | 86,075 | 748 | 85,701 | 2,664,006 | 30.9
50–51 | 0.009222 | 85,327 | 787 | 84,934 | 2,578,305 | 30.2
51–52 | 0.009736 | 84,540 | 823 | 84,129 | 2,493,371 | 29.5
52–53 | 0.010234 | 83,717 | 857 | 83,289 | 2,409,242 | 28.8
53–54 | 0.010708 | 82,861 | 887 | 82,417 | 2,325,953 | 28.1
54–55 | 0.011169 | 81,973 | 916 | 81,515 | 2,243,536 | 27.4
55–56 | 0.011625 | 81,058 | 942 | 80,587 | 2,162,021 | 26.7
56–57 | 0.012089 | 80,115 | 969 | 79,631 | 2,081,434 | 26.0
57–58 | 0.012565 | 79,147 | 994 | 78,650 | 2,001,803 | 25.3
58–59 | 0.013049 | 78,152 | 1,020 | 77,642 | 1,923,153 | 24.6
59–60 | 0.013530 | 77,133 | 1,044 | 76,611 | 1,845,511 | 23.9
60–61 | 0.014012 | 76,089 | 1,066 | 75,556 | 1,768,900 | 23.2
61–62 | 0.014486 | 75,023 | 1,087 | 74,479 | 1,693,344 | 22.6
62–63 | 0.014953 | 73,936 | 1,106 | 73,383 | 1,618,865 | 21.9
63–64 | 0.015426 | 72,830 | 1,123 | 72,269 | 1,545,482 | 21.2
64–65 | 0.015934 | 71,707 | 1,143 | 71,136 | 1,473,213 | 20.5
65–66 | 0.016471 | 70,564 | 1,162 | 69,983 | 1,402,077 | 19.9
66–67 | 0.017077 | 69,402 | 1,185 | 68,810 | 1,332,094 | 19.2
67–68 | 0.017838 | 68,217 | 1,217 | 67,609 | 1,263,285 | 18.5
68–69 | 0.018812 | 67,000 | 1,260 | 66,370 | 1,195,676 | 17.8
69–70 | 0.019991 | 65,740 | 1,314 | 65,083 | 1,129,306 | 17.2
70–71 | 0.021369 | 64,425 | 1,377 | 63,737 | 1,064,224 | 16.5
71–72 | 0.022893 | 63,049 | 1,443 | 62,327 | 1,000,486 | 15.9
72–73 | 0.024517 | 61,605 | 1,510 | 60,850 | 938,159 | 15.2
73–74 | 0.026183 | 60,095 | 1,573 | 59,308 | 877,309 | 14.6
74–75 | 0.027934 | 58,522 | 1,635 | 57,704 | 818,001 | 14.0
75–76 | 0.029827 | 56,887 | 1,697 | 56,038 | 760,297 | 13.4
76–77 | 0.032043 | 55,190 | 1,768 | 54,306 | 704,258 | 12.8
77–78 | 0.034770 | 53,422 | 1,857 | 52,493 | 649,953 | 12.2
78–79 | 0.038211 | 51,564 | 1,970 | 50,579 | 597,460 | 11.6
79–80 | 0.042392 | 49,594 | 2,102 | 48,543 | 546,881 | 11.0
80–81 | 0.047188 | 47,491 | 2,241 | 46,371 | 498,338 | 10.5
81–82 | 0.052041 | 45,250 | 2,355 | 44,073 | 451,967 | 10.0
82–83 | 0.056619 | 42,896 | 2,429 | 41,681 | 407,894 | 9.5
83–84 | 0.060789 | 40,467 | 2,460 | 39,237 | 366,213 | 9.0
84–85 | 0.064933 | 38,007 | 2,468 | 36,773 | 326,976 | 8.6
85–86 | 0.068371 | 35,539 | 2,430 | 34,324 | 290,203 | 8.2
86–87 | 0.074602 | 33,109 | 2,470 | 31,874 | 255,879 | 7.7
87–88 | 0.081306 | 30,639 | 2,491 | 29,394 | 224,005 | 7.3
88–89 | 0.088499 | 28,148 | 2,491 | 26,903 | 194,611 | 6.9
89–90 | 0.096195 | 25,657 | 2,468 | 24,423 | 167,709 | 6.5
90–91 | 0.104402 | 23,189 | 2,421 | 21,978 | 143,286 | 6.2
91–92 | 0.113121 | 20,768 | 2,349 | 19,593 | 121,307 | 5.8
92–93 | 0.122349 | 18,419 | 2,253 | 17,292 | 101,714 | 5.5
93–94 | 0.132073 | 16,165 | 2,135 | 15,098 | 84,422 | 5.2
94–95 | 0.142274 | 14,030 | 1,996 | 13,032 | 69,325 | 4.9
95–96 | 0.152921 | 12,034 | 1,840 | 11,114 | 56,292 | 4.7
96–97 | 0.163975 | 10,194 | 1,672 | 9,358 | 45,179 | 4.4
97–98 | 0.175385 | 8,522 | 1,495 | 7,775 | 35,821 | 4.2
98–99 | 0.187092 | 7,028 | 1,315 | 6,370 | 28,046 | 4.0
99–100 | 0.199026 | 5,713 | 1,137 | 5,144 | 21,675 | 3.8
100 and older | 1.000000 | 4,576 | 4,576 | 16,531 | 16,531 | 3.6

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 10

Life table for the Asian, non-Hispanic population: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table10.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.003434 | 100,000 | 343 | 99,691 | 8,521,152 | 85.2
1–2 | 0.000326 | 99,657 | 33 | 99,640 | 8,421,462 | 84.5
2–3 | 0.000072 | 99,624 | 7 | 99,620 | 8,321,822 | 83.5
3–4 | 0.000137 | 99,617 | 14 | 99,610 | 8,222,201 | 82.5
4–5 | 0.000119 | 99,603 | 12 | 99,597 | 8,122,591 | 81.5
5–6 | 0.000091 | 99,591 | 9 | 99,587 | 8,022,994 | 80.6
6–7 | 0.000087 | 99,582 | 9 | 99,578 | 7,923,407 | 79.6
7–8 | 0.000084 | 99,574 | 8 | 99,569 | 7,823,829 | 78.6
8–9 | 0.000080 | 99,565 | 8 | 99,561 | 7,724,260 | 77.6
9–10 | 0.000074 | 99,557 | 7 | 99,554 | 7,624,698 | 76.6
10–11 | 0.000071 | 99,550 | 7 | 99,546 | 7,525,145 | 75.6
11–12 | 0.000074 | 99,543 | 7 | 99,539 | 7,425,598 | 74.6
12–13 | 0.000090 | 99,536 | 9 | 99,531 | 7,326,059 | 73.6
13–14 | 0.000123 | 99,527 | 12 | 99,520 | 7,226,528 | 72.6
14–15 | 0.000168 | 99,514 | 17 | 99,506 | 7,127,007 | 71.6
15–16 | 0.000216 | 99,498 | 21 | 99,487 | 7,027,501 | 70.6
16–17 | 0.000263 | 99,476 | 26 | 99,463 | 6,928,015 | 69.6
17–18 | 0.000311 | 99,450 | 31 | 99,434 | 6,828,552 | 68.7
18–19 | 0.000360 | 99,419 | 36 | 99,401 | 6,729,117 | 67.7
19–20 | 0.000407 | 99,383 | 40 | 99,363 | 6,629,716 | 66.7
20–21 | 0.000456 | 99,343 | 45 | 99,320 | 6,530,353 | 65.7
21–22 | 0.000500 | 99,297 | 50 | 99,273 | 6,431,033 | 64.8
22–23 | 0.000527 | 99,248 | 52 | 99,222 | 6,331,761 | 63.8
23–24 | 0.000534 | 99,195 | 53 | 99,169 | 6,232,539 | 62.8
24–25 | 0.000527 | 99,143 | 52 | 99,116 | 6,133,370 | 61.9
25–26 | 0.000516 | 99,090 | 51 | 99,065 | 6,034,254 | 60.9
26–27 | 0.000508 | 99,039 | 50 | 99,014 | 5,935,189 | 59.9
27–28 | 0.000504 | 98,989 | 50 | 98,964 | 5,836,175 | 59.0
28–29 | 0.000507 | 98,939 | 50 | 98,914 | 5,737,211 | 58.0
29–30 | 0.000514 | 98,889 | 51 | 98,863 | 5,638,297 | 57.0
30–31 | 0.000523 | 98,838 | 52 | 98,812 | 5,539,434 | 56.0
31–32 | 0.000532 | 98,786 | 53 | 98,760 | 5,440,621 | 55.1
32–33 | 0.000542 | 98,734 | 54 | 98,707 | 5,341,861 | 54.1
33–34 | 0.000553 | 98,680 | 55 | 98,653 | 5,243,154 | 53.1
34–35 | 0.000566 | 98,626 | 56 | 98,598 | 5,144,501 | 52.2
35–36 | 0.000580 | 98,570 | 57 | 98,541 | 5,045,904 | 51.2
36–37 | 0.000600 | 98,513 | 59 | 98,483 | 4,947,362 | 50.2
37–38 | 0.000632 | 98,454 | 62 | 98,422 | 4,848,879 | 49.3
38–39 | 0.000680 | 98,391 | 67 | 98,358 | 4,750,457 | 48.3
39–40 | 0.000741 | 98,324 | 73 | 98,288 | 4,652,099 | 47.3
40–41 | 0.000813 | 98,252 | 80 | 98,212 | 4,553,811 | 46.3
41–42 | 0.000889 | 98,172 | 87 | 98,128 | 4,455,599 | 45.4
42–43 | 0.000959 | 98,084 | 94 | 98,037 | 4,357,472 | 44.4
43–44 | 0.001017 | 97,990 | 100 | 97,940 | 4,259,434 | 43.5
44–45 | 0.001069 | 97,891 | 105 | 97,838 | 4,161,494 | 42.5
45–46 | 0.001122 | 97,786 | 110 | 97,731 | 4,063,655 | 41.6
46–47 | 0.001190 | 97,676 | 116 | 97,618 | 3,965,924 | 40.6
47–48 | 0.001287 | 97,560 | 126 | 97,497 | 3,868,306 | 39.7
48–49 | 0.001419 | 97,434 | 138 | 97,365 | 3,770,809 | 38.7
49–50 | 0.001575 | 97,296 | 153 | 97,220 | 3,673,444 | 37.8
50–51 | 0.001745 | 97,143 | 170 | 97,058 | 3,576,224 | 36.8
51–52 | 0.001915 | 96,973 | 186 | 96,881 | 3,479,166 | 35.9
52–53 | 0.002076 | 96,788 | 201 | 96,687 | 3,382,285 | 34.9
53–54 | 0.002227 | 96,587 | 215 | 96,479 | 3,285,598 | 34.0
54–55 | 0.002380 | 96,372 | 229 | 96,257 | 3,189,119 | 33.1
55–56 | 0.002555 | 96,142 | 246 | 96,020 | 3,092,862 | 32.2
56–57 | 0.002762 | 95,897 | 265 | 95,764 | 2,996,842 | 31.3
57–58 | 0.002994 | 95,632 | 286 | 95,489 | 2,901,078 | 30.3
58–59 | 0.003245 | 95,346 | 309 | 95,191 | 2,805,589 | 29.4
59–60 | 0.003515 | 95,036 | 334 | 94,869 | 2,710,398 | 28.5
60–61 | 0.003793 | 94,702 | 359 | 94,522 | 2,615,529 | 27.6
61–62 | 0.004104 | 94,343 | 387 | 94,149 | 2,521,007 | 26.7
62–63 | 0.004482 | 93,956 | 421 | 93,745 | 2,426,858 | 25.8
63–64 | 0.004949 | 93,535 | 463 | 93,303 | 2,333,113 | 24.9
64–65 | 0.005498 | 93,072 | 512 | 92,816 | 2,239,809 | 24.1
65–66 | 0.006096 | 92,560 | 564 | 92,278 | 2,146,994 | 23.2
66–67 | 0.006722 | 91,996 | 618 | 91,687 | 2,054,716 | 22.3
67–68 | 0.007387 | 91,377 | 675 | 91,040 | 1,963,029 | 21.5
68–69 | 0.008094 | 90,702 | 734 | 90,335 | 1,871,989 | 20.6
69–70 | 0.008851 | 89,968 | 796 | 89,570 | 1,781,654 | 19.8
70–71 | 0.009684 | 89,172 | 864 | 88,740 | 1,692,084 | 19.0
71–72 | 0.010599 | 88,308 | 936 | 87,840 | 1,603,344 | 18.2
72–73 | 0.011599 | 87,372 | 1,013 | 86,866 | 1,515,504 | 17.3
73–74 | 0.012710 | 86,359 | 1,098 | 85,810 | 1,428,638 | 16.5
74–75 | 0.013974 | 85,261 | 1,191 | 84,666 | 1,342,828 | 15.7
75–76 | 0.015413 | 84,070 | 1,296 | 83,422 | 1,258,163 | 15.0
76–77 | 0.017059 | 82,774 | 1,412 | 82,068 | 1,174,741 | 14.2
77–78 | 0.019264 | 81,362 | 1,567 | 80,578 | 1,092,673 | 13.4
78–79 | 0.021599 | 79,795 | 1,724 | 78,933 | 1,012,095 | 12.7
79–80 | 0.024643 | 78,071 | 1,924 | 77,109 | 933,162 | 12.0
80–81 | 0.027731 | 76,147 | 2,112 | 75,091 | 856,053 | 11.2
81–82 | 0.031917 | 74,035 | 2,363 | 72,854 | 780,961 | 10.5
82–83 | 0.036417 | 71,673 | 2,610 | 70,367 | 708,107 | 9.9
83–84 | 0.041211 | 69,062 | 2,846 | 67,639 | 637,740 | 9.2
84–85 | 0.046836 | 66,216 | 3,101 | 64,666 | 570,100 | 8.6
85–86 | 0.052469 | 63,115 | 3,312 | 61,459 | 505,435 | 8.0
86–87 | 0.060526 | 59,803 | 3,620 | 57,994 | 443,976 | 7.4
87–88 | 0.069661 | 56,184 | 3,914 | 54,227 | 385,982 | 6.9
88–89 | 0.079969 | 52,270 | 4,180 | 50,180 | 331,755 | 6.3
89–90 | 0.091540 | 48,090 | 4,402 | 45,889 | 281,576 | 5.9
90–91 | 0.104453 | 43,688 | 4,563 | 41,406 | 235,687 | 5.4
91–92 | 0.118771 | 39,124 | 4,647 | 36,801 | 194,281 | 5.0
92–93 | 0.134534 | 34,478 | 4,638 | 32,158 | 157,480 | 4.6
93–94 | 0.151754 | 29,839 | 4,528 | 27,575 | 125,321 | 4.2
94–95 | 0.170409 | 25,311 | 4,313 | 23,154 | 97,746 | 3.9
95–96 | 0.190438 | 20,998 | 3,999 | 18,998 | 74,592 | 3.6
96–97 | 0.211737 | 16,999 | 3,599 | 15,199 | 55,594 | 3.3
97–98 | 0.234160 | 13,400 | 3,138 | 11,831 | 40,394 | 3.0
98–99 | 0.257520 | 10,262 | 2,643 | 8,941 | 28,564 | 2.8
99–100 | 0.281595 | 7,619 | 2,146 | 6,547 | 19,623 | 2.6
100 and older | 1.000000 | 5,474 | 5,474 | 13,076 | 13,076 | 2.4

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 11

Life table for Asian, non-Hispanic males: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table11.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.003771 | 100,000 | 377 | 99,656 | 8,316,517 | 83.2
1–2 | 0.000328 | 99,623 | 33 | 99,607 | 8,216,860 | 82.5
2–3 | 0.000103 | 99,590 | 10 | 99,585 | 8,117,254 | 81.5
3–4 | 0.000142 | 99,580 | 14 | 99,573 | 8,017,669 | 80.5
4–5 | 0.000145 | 99,566 | 14 | 99,559 | 7,918,096 | 79.5
5–6 | 0.000096 | 99,551 | 10 | 99,547 | 7,818,537 | 78.5
6–7 | 0.000087 | 99,542 | 9 | 99,537 | 7,718,991 | 77.5
7–8 | 0.000081 | 99,533 | 8 | 99,529 | 7,619,453 | 76.6
8–9 | 0.000077 | 99,525 | 8 | 99,521 | 7,519,924 | 75.6
9–10 | 0.000075 | 99,517 | 7 | 99,514 | 7,420,403 | 74.6
10–11 | 0.000077 | 99,510 | 8 | 99,506 | 7,320,889 | 73.6
11–12 | 0.000086 | 99,502 | 9 | 99,498 | 7,221,383 | 72.6
12–13 | 0.000104 | 99,494 | 10 | 99,489 | 7,121,885 | 71.6
13–14 | 0.000135 | 99,483 | 13 | 99,477 | 7,022,396 | 70.6
14–15 | 0.000175 | 99,470 | 17 | 99,461 | 6,922,919 | 69.6
15–16 | 0.000218 | 99,453 | 22 | 99,442 | 6,823,458 | 68.6
16–17 | 0.000263 | 99,431 | 26 | 99,418 | 6,724,016 | 67.6
17–18 | 0.000317 | 99,405 | 31 | 99,389 | 6,624,598 | 66.6
18–19 | 0.000379 | 99,373 | 38 | 99,355 | 6,525,209 | 65.7
19–20 | 0.000445 | 99,336 | 44 | 99,314 | 6,425,855 | 64.7
20–21 | 0.000513 | 99,292 | 51 | 99,266 | 6,326,541 | 63.7
21–22 | 0.000576 | 99,241 | 57 | 99,212 | 6,227,275 | 62.7
22–23 | 0.000624 | 99,183 | 62 | 99,152 | 6,128,063 | 61.8
23–24 | 0.000651 | 99,122 | 65 | 99,089 | 6,028,911 | 60.8
24–25 | 0.000665 | 99,057 | 66 | 99,024 | 5,929,822 | 59.9
25–26 | 0.000675 | 98,991 | 67 | 98,958 | 5,830,798 | 58.9
26–27 | 0.000686 | 98,924 | 68 | 98,890 | 5,731,840 | 57.9
27–28 | 0.000695 | 98,856 | 69 | 98,822 | 5,632,949 | 57.0
28–29 | 0.000702 | 98,788 | 69 | 98,753 | 5,534,127 | 56.0
29–30 | 0.000709 | 98,718 | 70 | 98,683 | 5,435,374 | 55.1
30–31 | 0.000716 | 98,648 | 71 | 98,613 | 5,336,691 | 54.1
31–32 | 0.000726 | 98,578 | 72 | 98,542 | 5,238,078 | 53.1
32–33 | 0.000738 | 98,506 | 73 | 98,470 | 5,139,536 | 52.2
33–34 | 0.000756 | 98,434 | 74 | 98,396 | 5,041,066 | 51.2
34–35 | 0.000779 | 98,359 | 77 | 98,321 | 4,942,669 | 50.3
35–36 | 0.000804 | 98,283 | 79 | 98,243 | 4,844,349 | 49.3
36–37 | 0.000835 | 98,204 | 82 | 98,163 | 4,746,105 | 48.3
37–38 | 0.000881 | 98,122 | 86 | 98,078 | 4,647,943 | 47.4
38–39 | 0.000947 | 98,035 | 93 | 97,989 | 4,549,864 | 46.4
39–40 | 0.001029 | 97,942 | 101 | 97,892 | 4,451,876 | 45.5
40–41 | 0.001125 | 97,842 | 110 | 97,787 | 4,353,984 | 44.5
41–42 | 0.001227 | 97,732 | 120 | 97,672 | 4,256,197 | 43.5
42–43 | 0.001325 | 97,612 | 129 | 97,547 | 4,158,526 | 42.6
43–44 | 0.001415 | 97,482 | 138 | 97,413 | 4,060,979 | 41.7
44–45 | 0.001501 | 97,344 | 146 | 97,271 | 3,963,565 | 40.7
45–46 | 0.001593 | 97,198 | 155 | 97,121 | 3,866,294 | 39.8
46–47 | 0.001703 | 97,043 | 165 | 96,961 | 3,769,173 | 38.8
47–48 | 0.001834 | 96,878 | 178 | 96,789 | 3,672,212 | 37.9
48–49 | 0.001988 | 96,701 | 192 | 96,604 | 3,575,423 | 37.0
49–50 | 0.002159 | 96,508 | 208 | 96,404 | 3,478,818 | 36.0
50–51 | 0.002340 | 96,300 | 225 | 96,187 | 3,382,414 | 35.1
51–52 | 0.002527 | 96,075 | 243 | 95,953 | 3,286,227 | 34.2
52–53 | 0.002722 | 95,832 | 261 | 95,701 | 3,190,274 | 33.3
53–54 | 0.002934 | 95,571 | 280 | 95,431 | 3,094,572 | 32.4
54–55 | 0.003174 | 95,291 | 302 | 95,139 | 2,999,142 | 31.5
55–56 | 0.003450 | 94,988 | 328 | 94,824 | 2,904,002 | 30.6
56–57 | 0.003761 | 94,660 | 356 | 94,482 | 2,809,178 | 29.7
57–58 | 0.004105 | 94,304 | 387 | 94,111 | 2,714,696 | 28.8
58–59 | 0.004466 | 93,917 | 419 | 93,708 | 2,620,585 | 27.9
59–60 | 0.004840 | 93,498 | 453 | 93,272 | 2,526,877 | 27.0
60–61 | 0.005228 | 93,045 | 486 | 92,802 | 2,433,606 | 26.2
61–62 | 0.005652 | 92,559 | 523 | 92,297 | 2,340,804 | 25.3
62–63 | 0.006129 | 92,036 | 564 | 91,754 | 2,248,506 | 24.4
63–64 | 0.006680 | 91,472 | 611 | 91,166 | 2,156,753 | 23.6
64–65 | 0.007305 | 90,861 | 664 | 90,529 | 2,065,587 | 22.7
65–66 | 0.007975 | 90,197 | 719 | 89,837 | 1,975,058 | 21.9
66–67 | 0.008686 | 89,478 | 777 | 89,089 | 1,885,221 | 21.1
67–68 | 0.009477 | 88,700 | 841 | 88,280 | 1,796,132 | 20.2
68–69 | 0.010368 | 87,860 | 911 | 87,404 | 1,707,852 | 19.4
69–70 | 0.011362 | 86,949 | 988 | 86,455 | 1,620,447 | 18.6
70–71 | 0.012479 | 85,961 | 1,073 | 85,425 | 1,533,992 | 17.8
71–72 | 0.013687 | 84,888 | 1,162 | 84,307 | 1,448,568 | 17.1
72–73 | 0.014941 | 83,726 | 1,251 | 83,101 | 1,364,261 | 16.3
73–74 | 0.016220 | 82,475 | 1,338 | 81,806 | 1,281,160 | 15.5
74–75 | 0.017573 | 81,138 | 1,426 | 80,425 | 1,199,353 | 14.8
75–76 | 0.019035 | 79,712 | 1,517 | 78,953 | 1,118,928 | 14.0
76–77 | 0.020729 | 78,194 | 1,621 | 77,384 | 1,039,975 | 13.3
77–78 | 0.023170 | 76,574 | 1,774 | 75,686 | 962,591 | 12.6
78–79 | 0.025851 | 74,799 | 1,934 | 73,833 | 886,905 | 11.9
79–80 | 0.029458 | 72,866 | 2,146 | 71,792 | 813,072 | 11.2
80–81 | 0.032966 | 70,719 | 2,331 | 69,554 | 741,280 | 10.5
81–82 | 0.037903 | 68,388 | 2,592 | 67,092 | 671,726 | 9.8
82–83 | 0.043184 | 65,796 | 2,841 | 64,375 | 604,634 | 9.2
83–84 | 0.048481 | 62,954 | 3,052 | 61,428 | 540,259 | 8.6
84–85 | 0.054560 | 59,902 | 3,268 | 58,268 | 478,831 | 8.0
85–86 | 0.061539 | 56,634 | 3,485 | 54,892 | 420,562 | 7.4
86–87 | 0.069355 | 53,149 | 3,686 | 51,306 | 365,671 | 6.9
87–88 | 0.079688 | 49,463 | 3,942 | 47,492 | 314,365 | 6.4
88–89 | 0.091290 | 45,521 | 4,156 | 43,443 | 266,873 | 5.9
89–90 | 0.104240 | 41,366 | 4,312 | 39,210 | 223,430 | 5.4
90–91 | 0.118595 | 37,054 | 4,394 | 34,856 | 184,220 | 5.0
91–92 | 0.134393 | 32,659 | 4,389 | 30,465 | 149,364 | 4.6
92–93 | 0.151638 | 28,270 | 4,287 | 26,127 | 118,899 | 4.2
93–94 | 0.170299 | 23,983 | 4,084 | 21,941 | 92,772 | 3.9
94–95 | 0.190304 | 19,899 | 3,787 | 18,006 | 70,831 | 3.6
95–96 | 0.211538 | 16,112 | 3,408 | 14,408 | 52,826 | 3.3
96–97 | 0.233841 | 12,704 | 2,971 | 11,218 | 38,418 | 3.0
97–98 | 0.257013 | 9,733 | 2,502 | 8,482 | 27,199 | 2.8
98–99 | 0.280819 | 7,232 | 2,031 | 6,216 | 18,717 | 2.6
99–100 | 0.304999 | 5,201 | 1,586 | 4,408 | 12,501 | 2.4
100 and older | 1.000000 | 3,615 | 3,615 | 8,093 | 8,093 | 2.2

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 12

Life table for Asian, non-Hispanic females: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table12.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.003074 | 100,000 | 307 | 99,728 | 8,705,092 | 87.1
1–2 | 0.000325 | 99,693 | 32 | 99,676 | 8,605,364 | 86.3
2–3 | 0.000040 | 99,660 | 4 | 99,658 | 8,505,688 | 85.3
3–4 | 0.000132 | 99,656 | 13 | 99,650 | 8,406,030 | 84.4
4–5 | 0.000091 | 99,643 | 9 | 99,639 | 8,306,380 | 83.4
5–6 | 0.000083 | 99,634 | 8 | 99,630 | 8,206,742 | 82.4
6–7 | 0.000084 | 99,626 | 8 | 99,622 | 8,107,112 | 81.4
7–8 | 0.000084 | 99,617 | 8 | 99,613 | 8,007,490 | 80.4
8–9 | 0.000083 | 99,609 | 8 | 99,605 | 7,907,877 | 79.4
9–10 | 0.000081 | 99,601 | 8 | 99,597 | 7,808,272 | 78.4
10–11 | 0.000079 | 99,593 | 8 | 99,589 | 7,708,675 | 77.4
11–12 | 0.000080 | 99,585 | 8 | 99,581 | 7,609,087 | 76.4
12–13 | 0.000087 | 99,577 | 9 | 99,573 | 7,509,506 | 75.4
13–14 | 0.000103 | 99,568 | 10 | 99,563 | 7,409,933 | 74.4
14–15 | 0.000124 | 99,558 | 12 | 99,552 | 7,310,370 | 73.4
15–16 | 0.000148 | 99,546 | 15 | 99,538 | 7,210,818 | 72.4
16–17 | 0.000171 | 99,531 | 17 | 99,522 | 7,111,280 | 71.4
17–18 | 0.000188 | 99,514 | 19 | 99,504 | 7,011,758 | 70.5
18–19 | 0.000198 | 99,495 | 20 | 99,485 | 6,912,253 | 69.5
19–20 | 0.000203 | 99,475 | 20 | 99,465 | 6,812,768 | 68.5
20–21 | 0.000206 | 99,455 | 21 | 99,445 | 6,713,303 | 67.5
21–22 | 0.000211 | 99,435 | 21 | 99,424 | 6,613,858 | 66.5
22–23 | 0.000217 | 99,414 | 22 | 99,403 | 6,514,433 | 65.5
23–24 | 0.000225 | 99,392 | 22 | 99,381 | 6,415,030 | 64.5
24–25 | 0.000234 | 99,370 | 23 | 99,358 | 6,315,649 | 63.6
25–26 | 0.000245 | 99,346 | 24 | 99,334 | 6,216,291 | 62.6
26–27 | 0.000255 | 99,322 | 25 | 99,310 | 6,116,957 | 61.6
27–28 | 0.000260 | 99,297 | 26 | 99,284 | 6,017,647 | 60.6
28–29 | 0.000260 | 99,271 | 26 | 99,258 | 5,918,364 | 59.6
29–30 | 0.000257 | 99,245 | 26 | 99,232 | 5,819,105 | 58.6
30–31 | 0.000255 | 99,220 | 25 | 99,207 | 5,719,873 | 57.6
31–32 | 0.000256 | 99,194 | 25 | 99,182 | 5,620,666 | 56.7
32–33 | 0.000265 | 99,169 | 26 | 99,156 | 5,521,484 | 55.7
33–34 | 0.000285 | 99,143 | 28 | 99,129 | 5,422,328 | 54.7
34–35 | 0.000312 | 99,114 | 31 | 99,099 | 5,323,200 | 53.7
35–36 | 0.000343 | 99,083 | 34 | 99,066 | 5,224,101 | 52.7
36–37 | 0.000375 | 99,049 | 37 | 99,031 | 5,125,034 | 51.7
37–38 | 0.000410 | 99,012 | 41 | 98,992 | 5,026,003 | 50.8
38–39 | 0.000447 | 98,972 | 44 | 98,950 | 4,927,011 | 49.8
39–40 | 0.000486 | 98,928 | 48 | 98,904 | 4,828,062 | 48.8
40–41 | 0.000533 | 98,880 | 53 | 98,853 | 4,729,158 | 47.8
41–42 | 0.000583 | 98,827 | 58 | 98,798 | 4,630,305 | 46.9
42–43 | 0.000626 | 98,769 | 62 | 98,738 | 4,531,507 | 45.9
43–44 | 0.000660 | 98,707 | 65 | 98,675 | 4,432,769 | 44.9
44–45 | 0.000688 | 98,642 | 68 | 98,608 | 4,334,094 | 43.9
45–46 | 0.000713 | 98,574 | 70 | 98,539 | 4,235,485 | 43.0
46–47 | 0.000750 | 98,504 | 74 | 98,467 | 4,136,946 | 42.0
47–48 | 0.000819 | 98,430 | 81 | 98,390 | 4,038,479 | 41.0
48–49 | 0.000929 | 98,350 | 91 | 98,304 | 3,940,089 | 40.1
49–50 | 0.001068 | 98,258 | 105 | 98,206 | 3,841,785 | 39.1
50–51 | 0.001224 | 98,153 | 120 | 98,093 | 3,743,579 | 38.1
51–52 | 0.001374 | 98,033 | 135 | 97,966 | 3,645,486 | 37.2
52–53 | 0.001504 | 97,899 | 147 | 97,825 | 3,547,520 | 36.2
53–54 | 0.001605 | 97,751 | 157 | 97,673 | 3,449,695 | 35.3
54–55 | 0.001691 | 97,594 | 165 | 97,512 | 3,352,022 | 34.3
55–56 | 0.001789 | 97,430 | 174 | 97,342 | 3,254,510 | 33.4
56–57 | 0.001916 | 97,255 | 186 | 97,162 | 3,157,168 | 32.5
57–58 | 0.002061 | 97,069 | 200 | 96,969 | 3,060,006 | 31.5
58–59 | 0.002226 | 96,869 | 216 | 96,761 | 2,963,037 | 30.6
59–60 | 0.002411 | 96,653 | 233 | 96,537 | 2,866,276 | 29.7
60–61 | 0.002602 | 96,420 | 251 | 96,295 | 2,769,739 | 28.7
61–62 | 0.002824 | 96,169 | 272 | 96,034 | 2,673,444 | 27.8
62–63 | 0.003122 | 95,898 | 299 | 95,748 | 2,577,411 | 26.9
63–64 | 0.003522 | 95,598 | 337 | 95,430 | 2,481,663 | 26.0
64–65 | 0.004008 | 95,262 | 382 | 95,071 | 2,386,233 | 25.0
65–66 | 0.004548 | 94,880 | 432 | 94,664 | 2,291,162 | 24.1
66–67 | 0.005106 | 94,448 | 482 | 94,207 | 2,196,498 | 23.3
67–68 | 0.005678 | 93,966 | 533 | 93,699 | 2,102,290 | 22.4
68–69 | 0.006250 | 93,433 | 584 | 93,141 | 2,008,591 | 21.5
69–70 | 0.006842 | 92,849 | 635 | 92,531 | 1,915,450 | 20.6
70–71 | 0.007479 | 92,213 | 690 | 91,869 | 1,822,919 | 19.8
71–72 | 0.008195 | 91,524 | 750 | 91,149 | 1,731,051 | 18.9
72–73 | 0.009020 | 90,774 | 819 | 90,364 | 1,639,902 | 18.1
73–74 | 0.010009 | 89,955 | 900 | 89,505 | 1,549,538 | 17.2
74–75 | 0.011195 | 89,055 | 997 | 88,556 | 1,460,033 | 16.4
75–76 | 0.012598 | 88,058 | 1,109 | 87,503 | 1,371,477 | 15.6
76–77 | 0.014190 | 86,948 | 1,234 | 86,331 | 1,283,974 | 14.8
77–78 | 0.016209 | 85,714 | 1,389 | 85,020 | 1,197,643 | 14.0
78–79 | 0.018294 | 84,325 | 1,543 | 83,554 | 1,112,623 | 13.2
79–80 | 0.020954 | 82,783 | 1,735 | 81,915 | 1,029,069 | 12.4
80–81 | 0.023803 | 81,048 | 1,929 | 80,083 | 947,154 | 11.7
81–82 | 0.027553 | 79,119 | 2,180 | 78,029 | 867,070 | 11.0
82–83 | 0.031601 | 76,939 | 2,431 | 75,723 | 789,042 | 10.3
83–84 | 0.036205 | 74,507 | 2,698 | 73,159 | 713,319 | 9.6
84–85 | 0.041679 | 71,810 | 2,993 | 70,313 | 640,160 | 8.9
85–86 | 0.046828 | 68,817 | 3,223 | 67,206 | 569,847 | 8.3
86–87 | 0.054562 | 65,594 | 3,579 | 63,805 | 502,641 | 7.7
87–88 | 0.063426 | 62,015 | 3,933 | 60,049 | 438,836 | 7.1
88–89 | 0.073538 | 58,082 | 4,271 | 55,946 | 378,787 | 6.5
89–90 | 0.085012 | 53,811 | 4,575 | 51,524 | 322,841 | 6.0
90–91 | 0.097955 | 49,236 | 4,823 | 46,825 | 271,317 | 5.5
91–92 | 0.112455 | 44,413 | 4,994 | 41,916 | 224,493 | 5.1
92–93 | 0.128581 | 39,419 | 5,068 | 36,885 | 182,577 | 4.6
93–94 | 0.146368 | 34,350 | 5,028 | 31,836 | 145,692 | 4.2
94–95 | 0.165814 | 29,323 | 4,862 | 26,891 | 113,856 | 3.9
95–96 | 0.186869 | 24,460 | 4,571 | 22,175 | 86,964 | 3.6
96–97 | 0.209433 | 19,890 | 4,166 | 17,807 | 64,789 | 3.3
97–98 | 0.233350 | 15,724 | 3,669 | 13,889 | 46,982 | 3.0
98–99 | 0.258414 | 12,055 | 3,115 | 10,497 | 33,093 | 2.7
99–100 | 0.284370 | 8,940 | 2,542 | 7,669 | 22,596 | 2.5
100 and older | 1.000000 | 6,398 | 6,398 | 14,927 | 14,927 | 2.3

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 13

Life table for the Black, non-Hispanic population: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table13.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.010872 | 100,000 | 1,087 | 99,070 | 7,398,556 | 74.0
1–2 | 0.000818 | 98,913 | 81 | 98,872 | 7,299,485 | 73.8
2–3 | 0.000529 | 98,832 | 52 | 98,806 | 7,200,613 | 72.9
3–4 | 0.000406 | 98,780 | 40 | 98,760 | 7,101,807 | 71.9
4–5 | 0.000338 | 98,739 | 33 | 98,723 | 7,003,048 | 70.9
5–6 | 0.000291 | 98,706 | 29 | 98,692 | 6,904,325 | 69.9
6–7 | 0.000267 | 98,677 | 26 | 98,664 | 6,805,633 | 69.0
7–8 | 0.000246 | 98,651 | 24 | 98,639 | 6,706,969 | 68.0
8–9 | 0.000218 | 98,627 | 21 | 98,616 | 6,608,330 | 67.0
9–10 | 0.000185 | 98,605 | 18 | 98,596 | 6,509,714 | 66.0
10–11 | 0.000161 | 98,587 | 16 | 98,579 | 6,411,118 | 65.0
11–12 | 0.000171 | 98,571 | 17 | 98,563 | 6,312,538 | 64.0
12–13 | 0.000243 | 98,555 | 24 | 98,543 | 6,213,975 | 63.1
13–14 | 0.000393 | 98,531 | 39 | 98,511 | 6,115,433 | 62.1
14–15 | 0.000595 | 98,492 | 59 | 98,462 | 6,016,922 | 61.1
15–16 | 0.000816 | 98,433 | 80 | 98,393 | 5,918,459 | 60.1
16–17 | 0.001023 | 98,353 | 101 | 98,302 | 5,820,066 | 59.2
17–18 | 0.001209 | 98,252 | 119 | 98,193 | 5,721,764 | 58.2
18–19 | 0.001364 | 98,133 | 134 | 98,066 | 5,623,571 | 57.3
19–20 | 0.001495 | 97,999 | 146 | 97,926 | 5,525,505 | 56.4
20–21 | 0.001632 | 97,853 | 160 | 97,773 | 5,427,579 | 55.5
21–22 | 0.001773 | 97,693 | 173 | 97,607 | 5,329,805 | 54.6
22–23 | 0.001879 | 97,520 | 183 | 97,428 | 5,232,199 | 53.7
23–24 | 0.001941 | 97,337 | 189 | 97,242 | 5,134,770 | 52.8
24–25 | 0.001972 | 97,148 | 192 | 97,052 | 5,037,528 | 51.9
25–26 | 0.001986 | 96,956 | 193 | 96,860 | 4,940,476 | 51.0
26–27 | 0.002013 | 96,764 | 195 | 96,666 | 4,843,616 | 50.1
27–28 | 0.002070 | 96,569 | 200 | 96,469 | 4,746,950 | 49.2
28–29 | 0.002168 | 96,369 | 209 | 96,265 | 4,650,481 | 48.3
29–30 | 0.002292 | 96,160 | 220 | 96,050 | 4,554,216 | 47.4
30–31 | 0.002417 | 95,940 | 232 | 95,824 | 4,458,166 | 46.5
31–32 | 0.002531 | 95,708 | 242 | 95,587 | 4,362,343 | 45.6
32–33 | 0.002639 | 95,466 | 252 | 95,340 | 4,266,756 | 44.7
33–34 | 0.002748 | 95,214 | 262 | 95,083 | 4,171,416 | 43.8
34–35 | 0.002867 | 94,952 | 272 | 94,816 | 4,076,333 | 42.9
35–36 | 0.003001 | 94,680 | 284 | 94,538 | 3,981,518 | 42.1
36–37 | 0.003156 | 94,396 | 298 | 94,247 | 3,886,980 | 41.2
37–38 | 0.003339 | 94,098 | 314 | 93,941 | 3,792,733 | 40.3
38–39 | 0.003543 | 93,784 | 332 | 93,617 | 3,698,793 | 39.4
39–40 | 0.003756 | 93,451 | 351 | 93,276 | 3,605,175 | 38.6
40–41 | 0.003985 | 93,100 | 371 | 92,915 | 3,511,900 | 37.7
41–42 | 0.004219 | 92,729 | 391 | 92,534 | 3,418,985 | 36.9
42–43 | 0.004428 | 92,338 | 409 | 92,134 | 3,326,451 | 36.0
43–44 | 0.004608 | 91,929 | 424 | 91,717 | 3,234,318 | 35.2
44–45 | 0.004779 | 91,505 | 437 | 91,287 | 3,142,601 | 34.3
45–46 | 0.004971 | 91,068 | 453 | 90,842 | 3,051,314 | 33.5
46–47 | 0.005205 | 90,616 | 472 | 90,380 | 2,960,472 | 32.7
47–48 | 0.005475 | 90,144 | 494 | 89,897 | 2,870,092 | 31.8
48–49 | 0.005776 | 89,650 | 518 | 89,391 | 2,780,195 | 31.0
49–50 | 0.006103 | 89,133 | 544 | 88,861 | 2,690,804 | 30.2
50–51 | 0.006445 | 88,589 | 571 | 88,303 | 2,601,943 | 29.4
51–52 | 0.006824 | 88,018 | 601 | 87,717 | 2,513,640 | 28.6
52–53 | 0.007268 | 87,417 | 635 | 87,099 | 2,425,923 | 27.8
53–54 | 0.007803 | 86,782 | 677 | 86,443 | 2,338,823 | 27.0
54–55 | 0.008430 | 86,104 | 726 | 85,742 | 2,252,380 | 26.2
55–56 | 0.009094 | 85,379 | 776 | 84,990 | 2,166,639 | 25.4
56–57 | 0.009802 | 84,602 | 829 | 84,188 | 2,081,648 | 24.6
57–58 | 0.010619 | 83,773 | 890 | 83,328 | 1,997,461 | 23.8
58–59 | 0.011552 | 82,883 | 957 | 82,405 | 1,914,133 | 23.1
59–60 | 0.012560 | 81,926 | 1,029 | 81,411 | 1,831,728 | 22.4
60–61 | 0.013587 | 80,897 | 1,099 | 80,347 | 1,750,317 | 21.6
61–62 | 0.014616 | 79,798 | 1,166 | 79,215 | 1,669,969 | 20.9
62–63 | 0.015683 | 78,631 | 1,233 | 78,015 | 1,590,755 | 20.2
63–64 | 0.016820 | 77,398 | 1,302 | 76,747 | 1,512,740 | 19.5
64–65 | 0.018042 | 76,096 | 1,373 | 75,410 | 1,435,993 | 18.9
65–66 | 0.019359 | 74,723 | 1,447 | 74,000 | 1,360,583 | 18.2
66–67 | 0.020774 | 73,277 | 1,522 | 72,516 | 1,286,583 | 17.6
67–68 | 0.022132 | 71,755 | 1,588 | 70,961 | 1,214,067 | 16.9
68–69 | 0.023509 | 70,166 | 1,650 | 69,342 | 1,143,107 | 16.3
69–70 | 0.024845 | 68,517 | 1,702 | 67,666 | 1,073,765 | 15.7
70–71 | 0.026397 | 66,815 | 1,764 | 65,933 | 1,006,099 | 15.1
71–72 | 0.028040 | 65,051 | 1,824 | 64,139 | 940,167 | 14.5
72–73 | 0.029737 | 63,227 | 1,880 | 62,287 | 876,028 | 13.9
73–74 | 0.031501 | 61,347 | 1,933 | 60,380 | 813,741 | 13.3
74–75 | 0.033285 | 59,414 | 1,978 | 58,425 | 753,361 | 12.7
75–76 | 0.035780 | 57,437 | 2,055 | 56,409 | 694,935 | 12.1
76–77 | 0.037469 | 55,381 | 2,075 | 54,344 | 638,527 | 11.5
77–78 | 0.041253 | 53,306 | 2,199 | 52,207 | 584,183 | 11.0
78–79 | 0.043886 | 51,107 | 2,243 | 49,986 | 531,976 | 10.4
79–80 | 0.048895 | 48,864 | 2,389 | 47,670 | 481,990 | 9.9
80–81 | 0.053113 | 46,475 | 2,468 | 45,241 | 434,320 | 9.3
81–82 | 0.058808 | 44,007 | 2,588 | 42,713 | 389,079 | 8.8
82–83 | 0.063828 | 41,419 | 2,644 | 40,097 | 346,367 | 8.4
83–84 | 0.068780 | 38,775 | 2,667 | 37,442 | 306,270 | 7.9
84–85 | 0.075594 | 36,108 | 2,730 | 34,743 | 268,828 | 7.4
85–86 | 0.082129 | 33,379 | 2,741 | 32,008 | 234,085 | 7.0
86–87 | 0.089447 | 30,637 | 2,740 | 29,267 | 202,077 | 6.6
87–88 | 0.098161 | 27,897 | 2,738 | 26,528 | 172,810 | 6.2
88–89 | 0.107565 | 25,158 | 2,706 | 23,805 | 146,282 | 5.8
89–90 | 0.117684 | 22,452 | 2,642 | 21,131 | 122,477 | 5.5
90–91 | 0.128536 | 19,810 | 2,546 | 18,537 | 101,346 | 5.1
91–92 | 0.140133 | 17,264 | 2,419 | 16,054 | 82,809 | 4.8
92–93 | 0.152480 | 14,844 | 2,263 | 13,713 | 66,755 | 4.5
93–94 | 0.165573 | 12,581 | 2,083 | 11,539 | 53,042 | 4.2
94–95 | 0.179397 | 10,498 | 1,883 | 9,556 | 41,503 | 4.0
95–96 | 0.193930 | 8,615 | 1,671 | 7,779 | 31,946 | 3.7
96–97 | 0.209134 | 6,944 | 1,452 | 6,218 | 24,167 | 3.5
97–98 | 0.224963 | 5,492 | 1,235 | 4,874 | 17,949 | 3.3
98–99 | 0.241358 | 4,256 | 1,027 | 3,743 | 13,075 | 3.1
99–100 | 0.258249 | 3,229 | 834 | 2,812 | 9,332 | 2.9
100 and older | 1.000000 | 2,395 | 2,395 | 6,520 | 6,520 | 2.7

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 14

Life table for Black, non-Hispanic males: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table14.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.011499 | 100,000 | 1,150 | 99,016 | 7,030,259 | 70.3
1–2 | 0.000819 | 98,850 | 81 | 98,810 | 6,931,244 | 70.1
2–3 | 0.000554 | 98,769 | 55 | 98,742 | 6,832,434 | 69.2
3–4 | 0.000395 | 98,714 | 39 | 98,695 | 6,733,692 | 68.2
4–5 | 0.000345 | 98,675 | 34 | 98,658 | 6,634,997 | 67.2
5–6 | 0.000294 | 98,641 | 29 | 98,627 | 6,536,339 | 66.3
6–7 | 0.000283 | 98,612 | 28 | 98,598 | 6,437,712 | 65.3
7–8 | 0.000267 | 98,584 | 26 | 98,571 | 6,339,114 | 64.3
8–9 | 0.000228 | 98,558 | 23 | 98,547 | 6,240,542 | 63.3
9–10 | 0.000171 | 98,536 | 17 | 98,527 | 6,141,996 | 62.3
10–11 | 0.000122 | 98,519 | 12 | 98,513 | 6,043,468 | 61.3
11–12 | 0.000129 | 98,507 | 13 | 98,500 | 5,944,956 | 60.4
12–13 | 0.000243 | 98,494 | 24 | 98,482 | 5,846,455 | 59.4
13–14 | 0.000492 | 98,470 | 48 | 98,446 | 5,747,973 | 58.4
14–15 | 0.000833 | 98,422 | 82 | 98,381 | 5,649,527 | 57.4
15–16 | 0.001204 | 98,340 | 118 | 98,280 | 5,551,147 | 56.4
16–17 | 0.001546 | 98,221 | 152 | 98,145 | 5,452,866 | 55.5
17–18 | 0.001845 | 98,069 | 181 | 97,979 | 5,354,721 | 54.6
18–19 | 0.002079 | 97,888 | 204 | 97,787 | 5,256,742 | 53.7
19–20 | 0.002265 | 97,685 | 221 | 97,574 | 5,158,955 | 52.8
20–21 | 0.002457 | 97,464 | 239 | 97,344 | 5,061,381 | 51.9
21–22 | 0.002652 | 97,224 | 258 | 97,095 | 4,964,037 | 51.1
22–23 | 0.002794 | 96,966 | 271 | 96,831 | 4,866,942 | 50.2
23–24 | 0.002864 | 96,696 | 277 | 96,557 | 4,770,111 | 49.3
24–25 | 0.002884 | 96,419 | 278 | 96,280 | 4,673,553 | 48.5
25–26 | 0.002877 | 96,141 | 277 | 96,002 | 4,577,274 | 47.6
26–27 | 0.002886 | 95,864 | 277 | 95,726 | 4,481,272 | 46.7
27–28 | 0.002939 | 95,587 | 281 | 95,447 | 4,385,546 | 45.9
28–29 | 0.003054 | 95,306 | 291 | 95,161 | 4,290,099 | 45.0
29–30 | 0.003209 | 95,015 | 305 | 94,863 | 4,194,939 | 44.2
30–31 | 0.003365 | 94,710 | 319 | 94,551 | 4,100,076 | 43.3
31–32 | 0.003504 | 94,392 | 331 | 94,226 | 4,005,525 | 42.4
32–33 | 0.003641 | 94,061 | 342 | 93,890 | 3,911,299 | 41.6
33–34 | 0.003782 | 93,718 | 354 | 93,541 | 3,817,409 | 40.7
34–35 | 0.003940 | 93,364 | 368 | 93,180 | 3,723,868 | 39.9
35–36 | 0.004122 | 92,996 | 383 | 92,804 | 3,630,688 | 39.0
36–37 | 0.004330 | 92,613 | 401 | 92,412 | 3,537,884 | 38.2
37–38 | 0.004563 | 92,212 | 421 | 92,001 | 3,445,472 | 37.4
38–39 | 0.004807 | 91,791 | 441 | 91,570 | 3,353,471 | 36.5
39–40 | 0.005049 | 91,350 | 461 | 91,119 | 3,261,901 | 35.7
40–41 | 0.005309 | 90,888 | 483 | 90,647 | 3,170,782 | 34.9
41–42 | 0.005580 | 90,406 | 504 | 90,154 | 3,080,134 | 34.1
42–43 | 0.005827 | 89,901 | 524 | 89,639 | 2,989,981 | 33.3
43–44 | 0.006048 | 89,378 | 541 | 89,107 | 2,900,341 | 32.5
44–45 | 0.006266 | 88,837 | 557 | 88,559 | 2,811,234 | 31.6
45–46 | 0.006511 | 88,280 | 575 | 87,993 | 2,722,675 | 30.8
46–47 | 0.006808 | 87,706 | 597 | 87,407 | 2,634,682 | 30.0
47–48 | 0.007156 | 87,109 | 623 | 86,797 | 2,547,275 | 29.2
48–49 | 0.007547 | 86,485 | 653 | 86,159 | 2,460,478 | 28.4
49–50 | 0.007971 | 85,832 | 684 | 85,490 | 2,374,320 | 27.7
50–51 | 0.008416 | 85,148 | 717 | 84,790 | 2,288,829 | 26.9
51–52 | 0.008901 | 84,432 | 751 | 84,056 | 2,204,039 | 26.1
52–53 | 0.009455 | 83,680 | 791 | 83,285 | 2,119,983 | 25.3
53–54 | 0.010108 | 82,889 | 838 | 82,470 | 2,036,699 | 24.6
54–55 | 0.010868 | 82,051 | 892 | 81,605 | 1,954,229 | 23.8
55–56 | 0.011667 | 81,159 | 947 | 80,686 | 1,872,623 | 23.1
56–57 | 0.012527 | 80,213 | 1,005 | 79,710 | 1,791,937 | 22.3
57–58 | 0.013548 | 79,208 | 1,073 | 78,671 | 1,712,227 | 21.6
58–59 | 0.014747 | 78,135 | 1,152 | 77,559 | 1,633,556 | 20.9
59–60 | 0.016064 | 76,982 | 1,237 | 76,364 | 1,555,997 | 20.2
60–61 | 0.017409 | 75,746 | 1,319 | 75,086 | 1,479,633 | 19.5
61–62 | 0.018749 | 74,427 | 1,395 | 73,729 | 1,404,547 | 18.9
62–63 | 0.020138 | 73,032 | 1,471 | 72,296 | 1,330,817 | 18.2
63–64 | 0.021613 | 71,561 | 1,547 | 70,788 | 1,258,521 | 17.6
64–65 | 0.023201 | 70,014 | 1,624 | 69,202 | 1,187,733 | 17.0
65–66 | 0.024928 | 68,390 | 1,705 | 67,537 | 1,118,531 | 16.4
66–67 | 0.026784 | 66,685 | 1,786 | 65,792 | 1,050,994 | 15.8
67–68 | 0.028526 | 64,899 | 1,851 | 63,973 | 985,202 | 15.2
68–69 | 0.030246 | 63,048 | 1,907 | 62,094 | 921,228 | 14.6
69–70 | 0.031945 | 61,141 | 1,953 | 60,164 | 859,134 | 14.1
70–71 | 0.033969 | 59,188 | 2,011 | 58,182 | 798,970 | 13.5
71–72 | 0.036058 | 57,177 | 2,062 | 56,146 | 740,788 | 13.0
72–73 | 0.038024 | 55,115 | 2,096 | 54,068 | 684,642 | 12.4
73–74 | 0.040261 | 53,020 | 2,135 | 51,952 | 630,574 | 11.9
74–75 | 0.042111 | 50,885 | 2,143 | 49,814 | 578,622 | 11.4
75–76 | 0.044905 | 48,742 | 2,189 | 47,648 | 528,808 | 10.8
76–77 | 0.046683 | 46,553 | 2,173 | 45,467 | 481,160 | 10.3
77–78 | 0.051523 | 44,380 | 2,287 | 43,237 | 435,693 | 9.8
78–79 | 0.053982 | 42,094 | 2,272 | 40,957 | 392,457 | 9.3
79–80 | 0.060084 | 39,821 | 2,393 | 38,625 | 351,499 | 8.8
80–81 | 0.064778 | 37,429 | 2,425 | 36,216 | 312,874 | 8.4
81–82 | 0.071872 | 35,004 | 2,516 | 33,746 | 276,658 | 7.9
82–83 | 0.077726 | 32,488 | 2,525 | 31,226 | 242,911 | 7.5
83–84 | 0.082836 | 29,963 | 2,482 | 28,722 | 211,686 | 7.1
84–85 | 0.090092 | 27,481 | 2,476 | 26,243 | 182,964 | 6.7
85–86 | 0.099883 | 25,005 | 2,498 | 23,756 | 156,720 | 6.3
86–87 | 0.104154 | 22,508 | 2,344 | 21,336 | 132,964 | 5.9
87–88 | 0.114280 | 20,163 | 2,304 | 19,011 | 111,628 | 5.5
88–89 | 0.125172 | 17,859 | 2,235 | 16,741 | 92,617 | 5.2
89–90 | 0.136844 | 15,624 | 2,138 | 14,555 | 75,876 | 4.9
90–91 | 0.149305 | 13,486 | 2,013 | 12,479 | 61,321 | 4.5
91–92 | 0.162552 | 11,472 | 1,865 | 10,540 | 48,842 | 4.3
92–93 | 0.176574 | 9,607 | 1,696 | 8,759 | 38,302 | 4.0
93–94 | 0.191346 | 7,911 | 1,514 | 7,154 | 29,543 | 3.7
94–95 | 0.206832 | 6,397 | 1,323 | 5,736 | 22,389 | 3.5
95–96 | 0.222984 | 5,074 | 1,131 | 4,508 | 16,654 | 3.3
96–97 | 0.239739 | 3,943 | 945 | 3,470 | 12,145 | 3.1
97–98 | 0.257024 | 2,997 | 770 | 2,612 | 8,675 | 2.9
98–99 | 0.274754 | 2,227 | 612 | 1,921 | 6,063 | 2.7
99–100 | 0.292831 | 1,615 | 473 | 1,379 | 4,142 | 2.6
100 and older | 1.000000 | 1,142 | 1,142 | 2,763 | 2,763 | 2.4

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 15

Life table for Black, non-Hispanic females: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table15.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.010224 | 100,000 | 1,022 | 99,128 | 7,762,525 | 77.6
1–2 | 0.000719 | 98,978 | 71 | 98,942 | 7,663,397 | 77.4
2–3 | 0.000437 | 98,907 | 43 | 98,885 | 7,564,455 | 76.5
3–4 | 0.000370 | 98,863 | 37 | 98,845 | 7,465,570 | 75.5
4–5 | 0.000290 | 98,827 | 29 | 98,812 | 7,366,725 | 74.5
5–6 | 0.000254 | 98,798 | 25 | 98,786 | 7,267,913 | 73.6
6–7 | 0.000222 | 98,773 | 22 | 98,762 | 7,169,127 | 72.6
7–8 | 0.000198 | 98,751 | 20 | 98,741 | 7,070,365 | 71.6
8–9 | 0.000179 | 98,731 | 18 | 98,723 | 6,971,624 | 70.6
9–10 | 0.000165 | 98,714 | 16 | 98,706 | 6,872,902 | 69.6
10–11 | 0.000158 | 98,698 | 16 | 98,690 | 6,774,196 | 68.6
11–12 | 0.000166 | 98,682 | 16 | 98,674 | 6,675,506 | 67.6
12–13 | 0.000196 | 98,665 | 19 | 98,656 | 6,576,833 | 66.7
13–14 | 0.000249 | 98,646 | 25 | 98,634 | 6,478,177 | 65.7
14–15 | 0.000321 | 98,622 | 32 | 98,606 | 6,379,543 | 64.7
15–16 | 0.000401 | 98,590 | 39 | 98,570 | 6,280,937 | 63.7
16–17 | 0.000480 | 98,550 | 47 | 98,527 | 6,182,367 | 62.7
17–18 | 0.000559 | 98,503 | 55 | 98,476 | 6,083,840 | 61.8
18–19 | 0.000637 | 98,448 | 63 | 98,417 | 5,985,365 | 60.8
19–20 | 0.000713 | 98,385 | 70 | 98,350 | 5,886,948 | 59.8
20–21 | 0.000796 | 98,315 | 78 | 98,276 | 5,788,598 | 58.9
21–22 | 0.000882 | 98,237 | 87 | 98,194 | 5,690,322 | 57.9
22–23 | 0.000955 | 98,150 | 94 | 98,103 | 5,592,128 | 57.0
23–24 | 0.001008 | 98,057 | 99 | 98,007 | 5,494,025 | 56.0
24–25 | 0.001049 | 97,958 | 103 | 97,906 | 5,396,018 | 55.1
25–26 | 0.001084 | 97,855 | 106 | 97,802 | 5,298,111 | 54.1
26–27 | 0.001128 | 97,749 | 110 | 97,694 | 5,200,310 | 53.2
27–28 | 0.001190 | 97,639 | 116 | 97,580 | 5,102,616 | 52.3
28–29 | 0.001273 | 97,522 | 124 | 97,460 | 5,005,035 | 51.3
29–30 | 0.001369 | 97,398 | 133 | 97,332 | 4,907,575 | 50.4
30–31 | 0.001467 | 97,265 | 143 | 97,193 | 4,810,244 | 49.5
31–32 | 0.001558 | 97,122 | 151 | 97,046 | 4,713,050 | 48.5
32–33 | 0.001644 | 96,971 | 159 | 96,891 | 4,616,004 | 47.6
33–34 | 0.001728 | 96,811 | 167 | 96,728 | 4,519,113 | 46.7
34–35 | 0.001819 | 96,644 | 176 | 96,556 | 4,422,385 | 45.8
35–36 | 0.001919 | 96,468 | 185 | 96,376 | 4,325,829 | 44.8
36–37 | 0.002037 | 96,283 | 196 | 96,185 | 4,229,453 | 43.9
37–38 | 0.002184 | 96,087 | 210 | 95,982 | 4,133,268 | 43.0
38–39 | 0.002361 | 95,877 | 226 | 95,764 | 4,037,286 | 42.1
39–40 | 0.002552 | 95,651 | 244 | 95,529 | 3,941,522 | 41.2
40–41 | 0.002759 | 95,407 | 263 | 95,275 | 3,845,993 | 40.3
41–42 | 0.002965 | 95,143 | 282 | 95,002 | 3,750,718 | 39.4
42–43 | 0.003146 | 94,861 | 298 | 94,712 | 3,655,716 | 38.5
43–44 | 0.003296 | 94,563 | 312 | 94,407 | 3,561,004 | 37.7
44–45 | 0.003433 | 94,251 | 324 | 94,089 | 3,466,597 | 36.8
45–46 | 0.003586 | 93,928 | 337 | 93,759 | 3,372,507 | 35.9
46–47 | 0.003772 | 93,591 | 353 | 93,414 | 3,278,748 | 35.0
47–48 | 0.003980 | 93,238 | 371 | 93,052 | 3,185,334 | 34.2
48–49 | 0.004204 | 92,867 | 390 | 92,672 | 3,092,281 | 33.3
49–50 | 0.004443 | 92,476 | 411 | 92,271 | 2,999,610 | 32.4
50–51 | 0.004692 | 92,066 | 432 | 91,849 | 2,907,339 | 31.6
51–52 | 0.004974 | 91,633 | 456 | 91,406 | 2,815,489 | 30.7
52–53 | 0.005319 | 91,178 | 485 | 90,935 | 2,724,084 | 29.9
53–54 | 0.005751 | 90,693 | 522 | 90,432 | 2,633,149 | 29.0
54–55 | 0.006263 | 90,171 | 565 | 89,889 | 2,542,717 | 28.2
55–56 | 0.006812 | 89,606 | 610 | 89,301 | 2,452,828 | 27.4
56–57 | 0.007392 | 88,996 | 658 | 88,667 | 2,363,527 | 26.6
57–58 | 0.008038 | 88,338 | 710 | 87,983 | 2,274,860 | 25.8
58–59 | 0.008747 | 87,628 | 766 | 87,245 | 2,186,877 | 25.0
59–60 | 0.009498 | 86,862 | 825 | 86,449 | 2,099,632 | 24.2
60–61 | 0.010261 | 86,037 | 883 | 85,595 | 2,013,183 | 23.4
61–62 | 0.011038 | 85,154 | 940 | 84,684 | 1,927,588 | 22.6
62–63 | 0.011856 | 84,214 | 998 | 83,715 | 1,842,904 | 21.9
63–64 | 0.012743 | 83,215 | 1,060 | 82,685 | 1,759,189 | 21.1
64–65 | 0.013707 | 82,155 | 1,126 | 81,592 | 1,676,504 | 20.4
65–66 | 0.014745 | 81,029 | 1,195 | 80,432 | 1,594,912 | 19.7
66–67 | 0.015860 | 79,834 | 1,266 | 79,201 | 1,514,480 | 19.0
67–68 | 0.016980 | 78,568 | 1,334 | 77,901 | 1,435,279 | 18.3
68–69 | 0.018165 | 77,234 | 1,403 | 76,532 | 1,357,378 | 17.6
69–70 | 0.019310 | 75,831 | 1,464 | 75,099 | 1,280,846 | 16.9
70–71 | 0.020605 | 74,367 | 1,532 | 73,601 | 1,205,747 | 16.2
71–72 | 0.022029 | 72,834 | 1,604 | 72,032 | 1,132,146 | 15.5
72–73 | 0.023653 | 71,230 | 1,685 | 70,388 | 1,060,114 | 14.9
73–74 | 0.025156 | 69,545 | 1,749 | 68,670 | 989,727 | 14.2
74–75 | 0.026976 | 67,796 | 1,829 | 66,881 | 921,056 | 13.6
75–76 | 0.029299 | 65,967 | 1,933 | 65,000 | 854,175 | 12.9
76–77 | 0.031015 | 64,034 | 1,986 | 63,041 | 789,175 | 12.3
77–78 | 0.034176 | 62,048 | 2,121 | 60,988 | 726,134 | 11.7
78–79 | 0.037091 | 59,927 | 2,223 | 58,816 | 665,146 | 11.1
79–80 | 0.041485 | 57,705 | 2,394 | 56,508 | 606,330 | 10.5
80–81 | 0.045606 | 55,311 | 2,522 | 54,050 | 549,822 | 9.9
81–82 | 0.050631 | 52,788 | 2,673 | 51,452 | 495,773 | 9.4
82–83 | 0.055472 | 50,116 | 2,780 | 48,726 | 444,321 | 8.9
83–84 | 0.060556 | 47,336 | 2,866 | 45,902 | 395,595 | 8.4
84–85 | 0.067266 | 44,469 | 2,991 | 42,973 | 349,693 | 7.9
85–86 | 0.072300 | 41,478 | 2,999 | 39,978 | 306,719 | 7.4
86–87 | 0.081103 | 38,479 | 3,121 | 36,919 | 266,741 | 6.9
87–88 | 0.089546 | 35,358 | 3,166 | 33,775 | 229,822 | 6.5
88–89 | 0.098720 | 32,192 | 3,178 | 30,603 | 196,047 | 6.1
89–90 | 0.108657 | 29,014 | 3,153 | 27,438 | 165,444 | 5.7
90–91 | 0.119384 | 25,861 | 3,087 | 24,318 | 138,007 | 5.3
91–92 | 0.130921 | 22,774 | 2,982 | 21,283 | 113,689 | 5.0
92–93 | 0.143282 | 19,792 | 2,836 | 18,374 | 92,406 | 4.7
93–94 | 0.156468 | 16,957 | 2,653 | 15,630 | 74,031 | 4.4
94–95 | 0.170473 | 14,303 | 2,438 | 13,084 | 58,401 | 4.1
95–96 | 0.185277 | 11,865 | 2,198 | 10,766 | 45,317 | 3.8
96–97 | 0.200845 | 9,667 | 1,942 | 8,696 | 34,551 | 3.6
97–98 | 0.217132 | 7,725 | 1,677 | 6,886 | 25,855 | 3.3
98–99 | 0.234075 | 6,048 | 1,416 | 5,340 | 18,969 | 3.1
99–100 | 0.251601 | 4,632 | 1,165 | 4,049 | 13,629 | 2.9
100 and older | 1.000000 | 3467 | 3467 | 9579 | 9579 | 2.8

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 16

Life table for the White, non-Hispanic population: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table16.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.004464 | 100,000 | 446 | 99,612 | 7,844,599 | 78.4
1–2 | 0.000307 | 99,554 | 31 | 99,538 | 7,744,987 | 77.8
2–3 | 0.000230 | 99,523 | 23 | 99,512 | 7,645,449 | 76.8
3–4 | 0.000173 | 99,500 | 17 | 99,492 | 7,545,937 | 75.8
4–5 | 0.000128 | 99,483 | 13 | 99,477 | 7,446,446 | 74.9
5–6 | 0.000130 | 99,470 | 13 | 99,464 | 7,346,969 | 73.9
6–7 | 0.000119 | 99,457 | 12 | 99,451 | 7,247,506 | 72.9
7–8 | 0.000110 | 99,445 | 11 | 99,440 | 7,148,054 | 71.9
8–9 | 0.000101 | 99,434 | 10 | 99,429 | 7,048,614 | 70.9
9–10 | 0.000091 | 99,424 | 9 | 99,420 | 6,949,185 | 69.9
10–11 | 0.000087 | 99,415 | 9 | 99,411 | 6,849,765 | 68.9
11–12 | 0.000095 | 99,407 | 9 | 99,402 | 6,750,354 | 67.9
12–13 | 0.000124 | 99,397 | 12 | 99,391 | 6,650,952 | 66.9
13–14 | 0.000178 | 99,385 | 18 | 99,376 | 6,551,561 | 65.9
14–15 | 0.000250 | 99,367 | 25 | 99,355 | 6,452,185 | 64.9
15–16 | 0.000328 | 99,342 | 33 | 99,326 | 6,352,830 | 63.9
16–17 | 0.000404 | 99,310 | 40 | 99,290 | 6,253,504 | 63.0
17–18 | 0.000476 | 99,270 | 47 | 99,246 | 6,154,215 | 62.0
18–19 | 0.000541 | 99,222 | 54 | 99,196 | 6,054,969 | 61.0
19–20 | 0.000602 | 99,169 | 60 | 99,139 | 5,955,773 | 60.1
20–21 | 0.000669 | 99,109 | 66 | 99,076 | 5,856,634 | 59.1
21–22 | 0.000740 | 99,043 | 73 | 99,006 | 5,757,558 | 58.1
22–23 | 0.000806 | 98,969 | 80 | 98,930 | 5,658,552 | 57.2
23–24 | 0.000865 | 98,890 | 86 | 98,847 | 5,559,623 | 56.2
24–25 | 0.000920 | 98,804 | 91 | 98,759 | 5,460,776 | 55.3
25–26 | 0.000974 | 98,713 | 96 | 98,665 | 5,362,017 | 54.3
26–27 | 0.001035 | 98,617 | 102 | 98,566 | 5,263,352 | 53.4
27–28 | 0.001113 | 98,515 | 110 | 98,460 | 5,164,786 | 52.4
28–29 | 0.001212 | 98,405 | 119 | 98,346 | 5,066,326 | 51.5
29–30 | 0.001322 | 98,286 | 130 | 98,221 | 4,967,980 | 50.5
30–31 | 0.001435 | 98,156 | 141 | 98,086 | 4,869,759 | 49.6
31–32 | 0.001541 | 98,015 | 151 | 97,940 | 4,771,673 | 48.7
32–33 | 0.001639 | 97,864 | 160 | 97,784 | 4,673,733 | 47.8
33–34 | 0.001728 | 97,704 | 169 | 97,619 | 4,575,949 | 46.8
34–35 | 0.001813 | 97,535 | 177 | 97,446 | 4,478,330 | 45.9
35–36 | 0.001900 | 97,358 | 185 | 97,266 | 4,380,884 | 45.0
36–37 | 0.001994 | 97,173 | 194 | 97,076 | 4,283,618 | 44.1
37–38 | 0.002096 | 96,979 | 203 | 96,878 | 4,186,542 | 43.2
38–39 | 0.002206 | 96,776 | 213 | 96,669 | 4,089,664 | 42.3
39–40 | 0.002322 | 96,563 | 224 | 96,451 | 3,992,995 | 41.4
40–41 | 0.002453 | 96,338 | 236 | 96,220 | 3,896,544 | 40.4
41–42 | 0.002589 | 96,102 | 249 | 95,978 | 3,800,324 | 39.5
42–43 | 0.002712 | 95,853 | 260 | 95,723 | 3,704,346 | 38.6
43–44 | 0.002819 | 95,593 | 269 | 95,459 | 3,608,623 | 37.7
44–45 | 0.002925 | 95,324 | 279 | 95,184 | 3,513,164 | 36.9
45–46 | 0.003052 | 95,045 | 290 | 94,900 | 3,417,980 | 36.0
46–47 | 0.003220 | 94,755 | 305 | 94,602 | 3,323,080 | 35.1
47–48 | 0.003430 | 94,450 | 324 | 94,288 | 3,228,478 | 34.2
48–49 | 0.003678 | 94,126 | 346 | 93,953 | 3,134,190 | 33.3
49–50 | 0.003949 | 93,780 | 370 | 93,595 | 3,040,237 | 32.4
50–51 | 0.004239 | 93,409 | 396 | 93,211 | 2,946,642 | 31.5
51–52 | 0.004551 | 93,013 | 423 | 92,802 | 2,853,431 | 30.7
52–53 | 0.004892 | 92,590 | 453 | 92,364 | 2,760,629 | 29.8
53–54 | 0.005276 | 92,137 | 486 | 91,894 | 2,668,266 | 29.0
54–55 | 0.005713 | 91,651 | 524 | 91,389 | 2,576,371 | 28.1
55–56 | 0.006174 | 91,128 | 563 | 90,846 | 2,484,982 | 27.3
56–57 | 0.006677 | 90,565 | 605 | 90,263 | 2,394,136 | 26.4
57–58 | 0.007265 | 89,960 | 654 | 89,633 | 2,303,873 | 25.6
58–59 | 0.007933 | 89,307 | 708 | 88,952 | 2,214,240 | 24.8
59–60 | 0.008641 | 88,598 | 766 | 88,215 | 2,125,287 | 24.0
60–61 | 0.009357 | 87,833 | 822 | 87,422 | 2,037,072 | 23.2
61–62 | 0.010065 | 87,011 | 876 | 86,573 | 1,949,650 | 22.4
62–63 | 0.010772 | 86,135 | 928 | 85,671 | 1,863,077 | 21.6
63–64 | 0.011497 | 85,207 | 980 | 84,717 | 1,777,406 | 20.9
64–65 | 0.012268 | 84,228 | 1,033 | 83,711 | 1,692,689 | 20.1
65–66 | 0.013107 | 83,194 | 1,090 | 82,649 | 1,608,978 | 19.3
66–67 | 0.014133 | 82,104 | 1,160 | 81,524 | 1,526,329 | 18.6
67–68 | 0.015111 | 80,943 | 1,223 | 80,332 | 1,444,805 | 17.8
68–69 | 0.016187 | 79,720 | 1,290 | 79,075 | 1,364,473 | 17.1
69–70 | 0.017385 | 78,430 | 1,364 | 77,748 | 1,285,398 | 16.4
70–71 | 0.018520 | 77,066 | 1,427 | 76,353 | 1,207,650 | 15.7
71–72 | 0.020024 | 75,639 | 1,515 | 74,882 | 1,131,297 | 15.0
72–73 | 0.021708 | 74,125 | 1,609 | 73,320 | 1,056,415 | 14.3
73–74 | 0.023809 | 72,515 | 1,727 | 71,652 | 983,095 | 13.6
74–75 | 0.026179 | 70,789 | 1,853 | 69,862 | 911,443 | 12.9
75–76 | 0.028867 | 68,936 | 1,990 | 67,941 | 841,581 | 12.2
76–77 | 0.031314 | 66,946 | 2,096 | 65,898 | 773,640 | 11.6
77–78 | 0.035519 | 64,849 | 2,303 | 63,698 | 707,742 | 10.9
78–79 | 0.038726 | 62,546 | 2,422 | 61,335 | 644,044 | 10.3
79–80 | 0.043387 | 60,124 | 2,609 | 58,820 | 582,709 | 9.7
80–81 | 0.047731 | 57,515 | 2,745 | 56,143 | 523,890 | 9.1
81–82 | 0.053724 | 54,770 | 2,942 | 53,299 | 467,747 | 8.5
82–83 | 0.060069 | 51,828 | 3,113 | 50,271 | 414,448 | 8.0
83–84 | 0.066685 | 48,714 | 3,249 | 47,090 | 364,177 | 7.5
84–85 | 0.074278 | 45,466 | 3,377 | 43,777 | 317,087 | 7.0
85–86 | 0.081722 | 42,089 | 3,440 | 40,369 | 273,310 | 6.5
86–87 | 0.092126 | 38,649 | 3,561 | 36,869 | 232,941 | 6.0
87–88 | 0.103621 | 35,089 | 3,636 | 33,271 | 196,072 | 5.6
88–89 | 0.116259 | 31,453 | 3,657 | 29,624 | 162,801 | 5.2
89–90 | 0.130083 | 27,796 | 3,616 | 25,988 | 133,177 | 4.8
90–91 | 0.145116 | 24,180 | 3,509 | 22,426 | 107,189 | 4.4
91–92 | 0.161365 | 20,671 | 3,336 | 19,003 | 84,763 | 4.1
92–93 | 0.178810 | 17,336 | 3,100 | 15,786 | 65,759 | 3.8
93–94 | 0.197403 | 14,236 | 2,810 | 12,831 | 49,974 | 3.5
94–95 | 0.217070 | 11,426 | 2,480 | 10,186 | 37,143 | 3.3
95–96 | 0.237703 | 8,946 | 2,126 | 7,882 | 26,957 | 3.0
96–97 | 0.259168 | 6,819 | 1,767 | 5,935 | 19,075 | 2.8
97–98 | 0.281299 | 5,052 | 1,421 | 4,341 | 13,139 | 2.6
98–99 | 0.303911 | 3,631 | 1,103 | 3,079 | 8,798 | 2.4
99–100 | 0.326799 | 2,527 | 826 | 2,114 | 5,719 | 2.3
100 and older | 1.000000 | 1,701 | 1,701 | 3,605 | 3,605 | 2.1

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 17

Life table for White, non-Hispanic males: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table17.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.004874 | 100,000 | 487 | 99,578 | 7,602,198 | 76.0
1–2 | 0.000430 | 99,513 | 43 | 99,491 | 7,502,620 | 75.4
2–3 | 0.000340 | 99,470 | 34 | 99,453 | 7,403,129 | 74.4
3–4 | 0.000237 | 99,436 | 24 | 99,424 | 7,303,676 | 73.5
4–5 | 0.000158 | 99,412 | 16 | 99,405 | 7,204,252 | 72.5
5–6 | 0.000159 | 99,397 | 16 | 99,389 | 7,104,847 | 71.5
6–7 | 0.000141 | 99,381 | 14 | 99,374 | 7,005,458 | 70.5
7–8 | 0.000127 | 99,367 | 13 | 99,361 | 6,906,084 | 69.5
8–9 | 0.000115 | 99,354 | 11 | 99,349 | 6,806,724 | 68.5
9–10 | 0.000103 | 99,343 | 10 | 99,338 | 6,707,375 | 67.5
10–11 | 0.000099 | 99,333 | 10 | 99,328 | 6,608,037 | 66.5
11–12 | 0.000112 | 99,323 | 11 | 99,317 | 6,508,709 | 65.5
12–13 | 0.000155 | 99,312 | 15 | 99,304 | 6,409,392 | 64.5
13–14 | 0.000232 | 99,296 | 23 | 99,285 | 6,310,088 | 63.5
14–15 | 0.000333 | 99,273 | 33 | 99,257 | 6,210,803 | 62.6
15–16 | 0.000442 | 99,240 | 44 | 99,218 | 6,111,546 | 61.6
16–17 | 0.000549 | 99,196 | 54 | 99,169 | 6,012,328 | 60.6
17–18 | 0.000650 | 99,142 | 64 | 99,110 | 5,913,159 | 59.6
18–19 | 0.000745 | 99,077 | 74 | 99,041 | 5,814,049 | 58.7
19–20 | 0.000835 | 99,004 | 83 | 98,962 | 5,715,009 | 57.7
20–21 | 0.000932 | 98,921 | 92 | 98,875 | 5,616,047 | 56.8
21–22 | 0.001034 | 98,829 | 102 | 98,778 | 5,517,172 | 55.8
22–23 | 0.001129 | 98,727 | 111 | 98,671 | 5,418,394 | 54.9
23–24 | 0.001214 | 98,615 | 120 | 98,555 | 5,319,723 | 53.9
24–25 | 0.001295 | 98,495 | 128 | 98,432 | 5,221,168 | 53.0
25–26 | 0.001372 | 98,368 | 135 | 98,300 | 5,122,736 | 52.1
26–27 | 0.001458 | 98,233 | 143 | 98,161 | 5,024,436 | 51.1
27–28 | 0.001562 | 98,090 | 153 | 98,013 | 4,926,274 | 50.2
28–29 | 0.001686 | 97,936 | 165 | 97,854 | 4,828,261 | 49.3
29–30 | 0.001822 | 97,771 | 178 | 97,682 | 4,730,407 | 48.4
30–31 | 0.001959 | 97,593 | 191 | 97,498 | 4,632,725 | 47.5
31–32 | 0.002088 | 97,402 | 203 | 97,300 | 4,535,227 | 46.6
32–33 | 0.002208 | 97,199 | 215 | 97,091 | 4,437,927 | 45.7
33–34 | 0.002320 | 96,984 | 225 | 96,872 | 4,340,836 | 44.8
34–35 | 0.002428 | 96,759 | 235 | 96,642 | 4,243,964 | 43.9
35–36 | 0.002538 | 96,524 | 245 | 96,402 | 4,147,322 | 43.0
36–37 | 0.002654 | 96,279 | 256 | 96,151 | 4,050,921 | 42.1
37–38 | 0.002775 | 96,024 | 266 | 95,890 | 3,954,769 | 41.2
38–39 | 0.002899 | 95,757 | 278 | 95,618 | 3,858,879 | 40.3
39–40 | 0.003025 | 95,480 | 289 | 95,335 | 3,763,260 | 39.4
40–41 | 0.003168 | 95,191 | 302 | 95,040 | 3,667,925 | 38.5
41–42 | 0.003316 | 94,889 | 315 | 94,732 | 3,572,885 | 37.7
42–43 | 0.003451 | 94,575 | 326 | 94,411 | 3,478,154 | 36.8
43–44 | 0.003570 | 94,248 | 336 | 94,080 | 3,383,742 | 35.9
44–45 | 0.003690 | 93,912 | 347 | 93,738 | 3,289,662 | 35.0
45–46 | 0.003837 | 93,565 | 359 | 93,386 | 3,195,924 | 34.2
46–47 | 0.004032 | 93,206 | 376 | 93,018 | 3,102,538 | 33.3
47–48 | 0.004277 | 92,830 | 397 | 92,632 | 3,009,520 | 32.4
48–49 | 0.004564 | 92,433 | 422 | 92,222 | 2,916,888 | 31.6
49–50 | 0.004878 | 92,012 | 449 | 91,787 | 2,824,665 | 30.7
50–51 | 0.005212 | 91,563 | 477 | 91,324 | 2,732,878 | 29.8
51–52 | 0.005576 | 91,086 | 508 | 90,832 | 2,641,554 | 29.0
52–53 | 0.005988 | 90,578 | 542 | 90,307 | 2,550,723 | 28.2
53–54 | 0.006470 | 90,035 | 583 | 89,744 | 2,460,416 | 27.3
54–55 | 0.007030 | 89,453 | 629 | 89,138 | 2,370,672 | 26.5
55–56 | 0.007627 | 88,824 | 677 | 88,485 | 2,281,534 | 25.7
56–57 | 0.008268 | 88,146 | 729 | 87,782 | 2,193,049 | 24.9
57–58 | 0.008998 | 87,418 | 787 | 87,024 | 2,105,267 | 24.1
58–59 | 0.009805 | 86,631 | 849 | 86,206 | 2,018,242 | 23.3
59–60 | 0.010646 | 85,782 | 913 | 85,325 | 1,932,036 | 22.5
60–61 | 0.011489 | 84,868 | 975 | 84,381 | 1,846,711 | 21.8
61–62 | 0.012326 | 83,893 | 1,034 | 83,376 | 1,762,330 | 21.0
62–63 | 0.013176 | 82,859 | 1,092 | 82,313 | 1,678,954 | 20.3
63–64 | 0.014067 | 81,768 | 1,150 | 81,193 | 1,596,640 | 19.5
64–65 | 0.015025 | 80,617 | 1,211 | 80,012 | 1,515,448 | 18.8
65–66 | 0.016066 | 79,406 | 1,276 | 78,768 | 1,435,436 | 18.1
66–67 | 0.017353 | 78,130 | 1,356 | 77,453 | 1,356,668 | 17.4
67–68 | 0.018538 | 76,775 | 1,423 | 76,063 | 1,279,215 | 16.7
68–69 | 0.019826 | 75,351 | 1,494 | 74,604 | 1,203,152 | 16.0
69–70 | 0.021223 | 73,857 | 1,568 | 73,074 | 1,128,548 | 15.3
70–71 | 0.022494 | 72,290 | 1,626 | 71,477 | 1,055,474 | 14.6
71–72 | 0.024204 | 70,664 | 1,710 | 69,809 | 983,997 | 13.9
72–73 | 0.026142 | 68,953 | 1,803 | 68,052 | 914,188 | 13.3
73–74 | 0.028487 | 67,151 | 1,913 | 66,194 | 846,136 | 12.6
74–75 | 0.031132 | 65,238 | 2,031 | 64,222 | 779,942 | 12.0
75–76 | 0.034057 | 63,207 | 2,153 | 62,131 | 715,719 | 11.3
76–77 | 0.036693 | 61,054 | 2,240 | 59,934 | 653,589 | 10.7
77–78 | 0.041451 | 58,814 | 2,438 | 57,595 | 593,654 | 10.1
78–79 | 0.044992 | 56,376 | 2,537 | 55,108 | 536,059 | 9.5
79–80 | 0.050395 | 53,840 | 2,713 | 52,483 | 480,951 | 8.9
80–81 | 0.055206 | 51,126 | 2,823 | 49,715 | 428,468 | 8.4
81–82 | 0.062319 | 48,304 | 3,010 | 46,799 | 378,753 | 7.8
82–83 | 0.069783 | 45,294 | 3,161 | 43,713 | 331,954 | 7.3
83–84 | 0.077130 | 42,133 | 3,250 | 40,508 | 288,241 | 6.8
84–85 | 0.085410 | 38,883 | 3,321 | 37,223 | 247,733 | 6.4
85–86 | 0.094734 | 35,562 | 3,369 | 33,878 | 210,510 | 5.9
86–87 | 0.104972 | 32,193 | 3,379 | 30,504 | 176,632 | 5.5
87–88 | 0.118212 | 28,814 | 3,406 | 27,111 | 146,129 | 5.1
88–89 | 0.132729 | 25,408 | 3,372 | 23,722 | 119,018 | 4.7
89–90 | 0.148545 | 22,035 | 3,273 | 20,399 | 95,297 | 4.3
90–91 | 0.165660 | 18,762 | 3,108 | 17,208 | 74,898 | 4.0
91–92 | 0.184048 | 15,654 | 2,881 | 14,213 | 57,690 | 3.7
92–93 | 0.203646 | 12,773 | 2,601 | 11,472 | 43,476 | 3.4
93–94 | 0.224362 | 10,172 | 2,282 | 9,031 | 32,004 | 3.1
94–95 | 0.246065 | 7,890 | 1,941 | 6,919 | 22,973 | 2.9
95–96 | 0.268592 | 5,948 | 1,598 | 5,149 | 16,054 | 2.7
96–97 | 0.291751 | 4,351 | 1,269 | 3,716 | 10,905 | 2.5
97–98 | 0.315326 | 3,081 | 972 | 2,595 | 7,189 | 2.3
98–99 | 0.339082 | 2,110 | 715 | 1,752 | 4,593 | 2.2
99–100 | 0.362780 | 1,394 | 506 | 1,141 | 2,841 | 2.0
100 and older | 1.000000 | 888 | 888 | 1,700 | 1,700 | 1.9

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 18

Life table for White, non-Hispanic females: United States, 2023

Spreadsheet version available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/74-06/Table18.xlsx .
Age (years) | Probability of dying between ages x and x + 1 | Number surviving to age x | Number dying between ages x and x + 1 | Person-years lived between ages x and x + 1 | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | q _x _ | l _x _ | d _x _ | L _x _ | T _x _ | e _x _
0–1 | 0.004033 | 100,000 | 403 | 99,648 | 8,094,750 | 80.9
1–2 | 0.000213 | 99,597 | 21 | 99,586 | 7,995,102 | 80.3
2–3 | 0.000145 | 99,575 | 14 | 99,568 | 7,895,516 | 79.3
3–4 | 0.000118 | 99,561 | 12 | 99,555 | 7,795,948 | 78.3
4–5 | 0.000099 | 99,549 | 10 | 99,544 | 7,696,393 | 77.3
5–6 | 0.000100 | 99,539 | 10 | 99,534 | 7,596,848 | 76.3
6–7 | 0.000095 | 99,529 | 9 | 99,525 | 7,497,314 | 75.3
7–8 | 0.000090 | 99,520 | 9 | 99,515 | 7,397,789 | 74.3
8–9 | 0.000085 | 99,511 | 8 | 99,507 | 7,298,274 | 73.3
9–10 | 0.000078 | 99,502 | 8 | 99,499 | 7,198,767 | 72.3
10–11 | 0.000074 | 99,495 | 7 | 99,491 | 7,099,269 | 71.4
11–12 | 0.000078 | 99,487 | 8 | 99,483 | 6,999,778 | 70.4
12–13 | 0.000093 | 99,480 | 9 | 99,475 | 6,900,294 | 69.4
13–14 | 0.000123 | 99,470 | 12 | 99,464 | 6,800,819 | 68.4
14–15 | 0.000164 | 99,458 | 16 | 99,450 | 6,701,355 | 67.4
15–16 | 0.000208 | 99,442 | 21 | 99,431 | 6,601,905 | 66.4
16–17 | 0.000251 | 99,421 | 25 | 99,409 | 6,502,474 | 65.4
17–18 | 0.000291 | 99,396 | 29 | 99,382 | 6,403,065 | 64.4
18–19 | 0.000325 | 99,367 | 32 | 99,351 | 6,303,684 | 63.4
19–20 | 0.000356 | 99,335 | 35 | 99,317 | 6,204,333 | 62.5
20–21 | 0.000391 | 99,299 | 39 | 99,280 | 6,105,016 | 61.5
21–22 | 0.000430 | 99,261 | 43 | 99,239 | 6,005,736 | 60.5
22–23 | 0.000466 | 99,218 | 46 | 99,195 | 5,906,496 | 59.5
23–24 | 0.000497 | 99,172 | 49 | 99,147 | 5,807,302 | 58.6
24–25 | 0.000527 | 99,122 | 52 | 99,096 | 5,708,155 | 57.6
25–26 | 0.000556 | 99,070 | 55 | 99,043 | 5,609,058 | 56.6
26–27 | 0.000592 | 99,015 | 59 | 98,986 | 5,510,016 | 55.6
27–28 | 0.000645 | 98,956 | 64 | 98,924 | 5,411,030 | 54.7
28–29 | 0.000719 | 98,892 | 71 | 98,857 | 5,312,106 | 53.7
29–30 | 0.000805 | 98,821 | 80 | 98,782 | 5,213,249 | 52.8
30–31 | 0.000895 | 98,742 | 88 | 98,698 | 5,114,467 | 51.8
31–32 | 0.000980 | 98,653 | 97 | 98,605 | 5,015,770 | 50.8
32–33 | 0.001056 | 98,557 | 104 | 98,505 | 4,917,164 | 49.9
33–34 | 0.001122 | 98,453 | 111 | 98,397 | 4,818,660 | 48.9
34–35 | 0.001184 | 98,342 | 116 | 98,284 | 4,720,262 | 48.0
35–36 | 0.001247 | 98,226 | 123 | 98,165 | 4,621,978 | 47.1
36–37 | 0.001318 | 98,103 | 129 | 98,039 | 4,523,814 | 46.1
37–38 | 0.001400 | 97,974 | 137 | 97,905 | 4,425,775 | 45.2
38–39 | 0.001496 | 97,837 | 146 | 97,764 | 4,327,870 | 44.2
39–40 | 0.001601 | 97,690 | 156 | 97,612 | 4,230,106 | 43.3
40–41 | 0.001720 | 97,534 | 168 | 97,450 | 4,132,494 | 42.4
41–42 | 0.001843 | 97,366 | 179 | 97,276 | 4,035,044 | 41.4
42–43 | 0.001953 | 97,187 | 190 | 97,092 | 3,937,767 | 40.5
43–44 | 0.002048 | 96,997 | 199 | 96,898 | 3,840,675 | 39.6
44–45 | 0.002140 | 96,798 | 207 | 96,695 | 3,743,778 | 38.7
45–46 | 0.002248 | 96,591 | 217 | 96,483 | 3,647,083 | 37.8
46–47 | 0.002390 | 96,374 | 230 | 96,259 | 3,550,600 | 36.8
47–48 | 0.002566 | 96,144 | 247 | 96,020 | 3,454,341 | 35.9
48–49 | 0.002773 | 95,897 | 266 | 95,764 | 3,358,321 | 35.0
49–50 | 0.002998 | 95,631 | 287 | 95,488 | 3,262,557 | 34.1
50–51 | 0.003242 | 95,344 | 309 | 95,190 | 3,167,069 | 33.2
51–52 | 0.003501 | 95,035 | 333 | 94,869 | 3,071,879 | 32.3
52–53 | 0.003770 | 94,703 | 357 | 94,524 | 2,977,010 | 31.4
53–54 | 0.004057 | 94,346 | 383 | 94,154 | 2,882,486 | 30.6
54–55 | 0.004375 | 93,963 | 411 | 93,757 | 2,788,332 | 29.7
55–56 | 0.004708 | 93,552 | 440 | 93,331 | 2,694,575 | 28.8
56–57 | 0.005081 | 93,111 | 473 | 92,875 | 2,601,243 | 27.9
57–58 | 0.005536 | 92,638 | 513 | 92,382 | 2,508,368 | 27.1
58–59 | 0.006076 | 92,125 | 560 | 91,845 | 2,415,987 | 26.2
59–60 | 0.006661 | 91,566 | 610 | 91,261 | 2,324,141 | 25.4
60–61 | 0.007263 | 90,956 | 661 | 90,625 | 2,232,881 | 24.5
61–62 | 0.007854 | 90,295 | 709 | 89,940 | 2,142,255 | 23.7
62–63 | 0.008434 | 89,586 | 756 | 89,208 | 2,052,315 | 22.9
63–64 | 0.009013 | 88,830 | 801 | 88,430 | 1,963,107 | 22.1
64–65 | 0.009619 | 88,030 | 847 | 87,606 | 1,874,677 | 21.3
65–66 | 0.010283 | 87,183 | 897 | 86,735 | 1,787,071 | 20.5
66–67 | 0.011097 | 86,286 | 957 | 85,808 | 1,700,336 | 19.7
67–68 | 0.011907 | 85,329 | 1,016 | 84,821 | 1,614,528 | 18.9
68–69 | 0.012819 | 84,313 | 1,081 | 83,772 | 1,529,708 | 18.1
69–70 | 0.013872 | 83,232 | 1,155 | 82,655 | 1,445,935 | 17.4
70–71 | 0.014901 | 82,078 | 1,223 | 81,466 | 1,363,280 | 16.6
71–72 | 0.016259 | 80,854 | 1,315 | 80,197 | 1,281,814 | 15.9
72–73 | 0.017764 | 79,540 | 1,413 | 78,833 | 1,201,617 | 15.1
73–74 | 0.019694 | 78,127 | 1,539 | 77,358 | 1,122,784 | 14.4
74–75 | 0.021872 | 76,588 | 1,675 | 75,751 | 1,045,426 | 13.6
75–76 | 0.024388 | 74,913 | 1,827 | 74,000 | 969,675 | 12.9
76–77 | 0.026689 | 73,086 | 1,951 | 72,111 | 895,676 | 12.3
77–78 | 0.030465 | 71,136 | 2,167 | 70,052 | 823,565 | 11.6
78–79 | 0.033447 | 68,968 | 2,307 | 67,815 | 753,513 | 10.9
79–80 | 0.037594 | 66,662 | 2,506 | 65,409 | 685,698 | 10.3
80–81 | 0.041660 | 64,156 | 2,673 | 62,819 | 620,290 | 9.7
81–82 | 0.046916 | 61,483 | 2,885 | 60,040 | 557,470 | 9.1
82–83 | 0.052568 | 58,598 | 3,080 | 57,058 | 497,430 | 8.5
83–84 | 0.058838 | 55,518 | 3,267 | 53,885 | 440,372 | 7.9
84–85 | 0.066102 | 52,251 | 3,454 | 50,524 | 386,487 | 7.4
85–86 | 0.072772 | 48,797 | 3,551 | 47,022 | 335,963 | 6.9
86–87 | 0.082533 | 45,246 | 3,734 | 43,379 | 288,941 | 6.4
87–88 | 0.093396 | 41,512 | 3,877 | 39,573 | 245,562 | 5.9
88–89 | 0.105432 | 37,635 | 3,968 | 35,651 | 205,989 | 5.5
89–90 | 0.118698 | 33,667 | 3,996 | 31,669 | 170,338 | 5.1
90–91 | 0.133236 | 29,671 | 3,953 | 27,694 | 138,669 | 4.7
91–92 | 0.149071 | 25,718 | 3,834 | 23,801 | 110,975 | 4.3
92–93 | 0.166201 | 21,884 | 3,637 | 20,065 | 87,174 | 4.0
93–94 | 0.184597 | 18,247 | 3,368 | 16,563 | 67,109 | 3.7
94–95 | 0.204199 | 14,878 | 3,038 | 13,359 | 50,546 | 3.4
95–96 | 0.224912 | 11,840 | 2,663 | 10,509 | 37,187 | 3.1
96–97 | 0.246605 | 9,177 | 2,263 | 8,046 | 26,678 | 2.9
97–98 | 0.269116 | 6,914 | 1,861 | 5,984 | 18,633 | 2.7
98–99 | 0.292252 | 5,053 | 1,477 | 4,315 | 12,649 | 2.5
99–100 | 0.315797 | 3,577 | 1,129 | 3,012 | 8,334 | 2.3
100 and older | 1.000000 | 2,447 | 2,447 | 5,322 | 5,322 | 2.2

NOTE: This life table is based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table A

Expectation of life, by age, Hispanic origin and race, and sex: United States, 2023

Age | All origins | | | Hispanic | | | Non-Hispanic
Age | All origins | | | Hispanic | | | American Indian and Alaska Native | | | Asian | | | Black | | | White
Age | Total | Male | Female | Total | Male | Female | Total | Male | Female | Total | Male | Female | Total | Male | Female | Total | Male | Female
0 | 78.4 | 75.8 | 81.1 | 81.3 | 78.5 | 84.0 | 70.1 | 66.7 | 73.5 | 85.2 | 83.2 | 87.1 | 74.0 | 70.3 | 77.6 | 78.4 | 76.0 | 80.9
1 | 77.9 | 75.3 | 80.5 | 80.7 | 77.9 | 83.4 | 69.7 | 66.4 | 73.1 | 84.5 | 82.5 | 86.3 | 73.8 | 70.1 | 77.4 | 77.8 | 75.4 | 80.3
5 | 73.9 | 71.4 | 76.6 | 76.8 | 74.0 | 79.4 | 65.9 | 62.6 | 69.3 | 80.6 | 78.5 | 82.4 | 69.9 | 66.3 | 73.6 | 73.9 | 71.5 | 76.3
10 | 69.0 | 66.4 | 71.6 | 71.8 | 69.0 | 74.5 | 60.9 | 57.6 | 64.3 | 75.6 | 73.6 | 77.4 | 65.0 | 61.3 | 68.6 | 68.9 | 66.5 | 71.4
15 | 64.0 | 61.5 | 66.7 | 66.9 | 64.1 | 69.5 | 56.0 | 52.8 | 59.4 | 70.6 | 68.6 | 72.4 | 60.1 | 56.4 | 63.7 | 63.9 | 61.6 | 66.4
20 | 59.2 | 56.7 | 61.8 | 62.0 | 59.3 | 64.6 | 51.4 | 48.2 | 54.8 | 65.7 | 63.7 | 67.5 | 55.5 | 51.9 | 58.9 | 59.1 | 56.8 | 61.5
25 | 54.5 | 52.1 | 56.9 | 57.3 | 54.7 | 59.7 | 47.0 | 43.8 | 50.3 | 60.9 | 58.9 | 62.6 | 51.0 | 47.6 | 54.1 | 54.3 | 52.1 | 56.6
30 | 49.8 | 47.5 | 52.1 | 52.6 | 50.2 | 54.9 | 42.8 | 39.8 | 45.9 | 56.0 | 54.1 | 57.6 | 46.5 | 43.3 | 49.5 | 49.6 | 47.5 | 51.8
35 | 45.2 | 43.1 | 47.4 | 48.0 | 45.7 | 50.1 | 39.0 | 36.2 | 41.8 | 51.2 | 49.3 | 52.7 | 42.1 | 39.0 | 44.8 | 45.0 | 43.0 | 47.1
40 | 40.7 | 38.6 | 42.7 | 43.4 | 41.2 | 45.3 | 35.3 | 32.8 | 37.8 | 46.3 | 44.5 | 47.8 | 37.7 | 34.9 | 40.3 | 40.4 | 38.5 | 42.4
45 | 36.2 | 34.3 | 38.0 | 38.9 | 36.8 | 40.6 | 31.7 | 29.3 | 34.0 | 41.6 | 39.8 | 43.0 | 33.5 | 30.8 | 35.9 | 36.0 | 34.2 | 37.8
50 | 31.8 | 30.0 | 33.5 | 34.3 | 32.4 | 35.9 | 28.3 | 26.2 | 30.2 | 36.8 | 35.1 | 38.1 | 29.4 | 26.9 | 31.6 | 31.5 | 29.8 | 33.2
55 | 27.5 | 25.8 | 29.0 | 29.9 | 28.1 | 31.3 | 25.0 | 23.2 | 26.7 | 32.2 | 30.6 | 33.4 | 25.4 | 23.1 | 27.4 | 27.3 | 25.7 | 28.8
60 | 23.4 | 21.9 | 24.8 | 25.6 | 24.0 | 26.9 | 21.9 | 20.4 | 23.2 | 27.6 | 26.2 | 28.7 | 21.6 | 19.5 | 23.4 | 23.2 | 21.8 | 24.5
65 | 19.5 | 18.2 | 20.7 | 21.6 | 20.2 | 22.6 | 18.9 | 17.8 | 19.9 | 23.2 | 21.9 | 24.1 | 18.2 | 16.4 | 19.7 | 19.3 | 18.1 | 20.5
70 | 15.9 | 14.7 | 16.8 | 17.7 | 16.5 | 18.5 | 16.0 | 15.3 | 16.5 | 19.0 | 17.8 | 19.8 | 15.1 | 13.5 | 16.2 | 15.7 | 14.6 | 16.6
75 | 12.4 | 11.5 | 13.2 | 14.0 | 13.0 | 14.6 | 13.2 | 12.9 | 13.4 | 15.0 | 14.0 | 15.6 | 12.1 | 10.8 | 12.9 | 12.2 | 11.3 | 12.9
80 | 9.3 | 8.5 | 9.9 | 10.7 | 9.8 | 11.0 | 10.6 | 10.5 | 10.5 | 11.2 | 10.5 | 11.7 | 9.3 | 8.4 | 9.9 | 9.1 | 8.4 | 9.7
85 | 6.7 | 6.1 | 7.0 | 7.8 | 7.1 | 7.9 | 8.4 | 8.5 | 8.2 | 8.0 | 7.4 | 8.3 | 7.0 | 6.3 | 7.4 | 6.5 | 5.9 | 6.9
90 | 4.6 | 4.1 | 4.8 | 5.4 | 4.9 | 5.4 | 6.6 | 6.7 | 6.2 | 5.4 | 5.0 | 5.5 | 5.1 | 4.5 | 5.3 | 4.4 | 4.0 | 4.7
95 | 3.1 | 2.8 | 3.3 | 3.7 | 3.4 | 3.6 | 5.2 | 5.4 | 4.7 | 3.6 | 3.3 | 3.6 | 3.7 | 3.3 | 3.8 | 3.0 | 2.7 | 3.1
100 | 2.2 | 2.0 | 2.3 | 2.6 | 2.4 | 2.5 | 4.1 | 4.5 | 3.6 | 2.4 | 2.2 | 2.3 | 2.7 | 2.4 | 2.8 | 2.1 | 1.9 | 2.2

NOTES: Life tables by Hispanic origin and race are based on death rates that have been adjusted for race and ethnicity misclassification on death certificates; see Technical Notes in this report. Hispanic people may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Life expectancy at birth (e_0_) for 2023 for the total population was 78.4 years. This represents the average number of years that the members of the hypothetical life table cohort can expect to live at the time of birth (Table A).

### Survivors to specified ages

Another way of assessing the longevity of the period life table cohort is by determining the proportion that survives to specified ages. The l_x_ column of the life table provides the data for computing this proportion. Table B summarizes the number of survivors by age, Hispanic origin and race, and sex. To illustrate, 57,812 people out of the original 2023 hypothetical life table cohort of 100,000 (or 57.8%) were alive at exact age 80. In other words, the probability that a person will survive from birth to age 80, given 2023 age-specific mortality, is 57.8%. Probabilities of survival can be calculated at any age by dividing the number of survivors at the terminal age by the number at the beginning age. For example, to calculate the probability of surviving from age 20 to age 85, divide the number of survivors at age 85 (42,699) by the number of survivors at age 20 (98,901), which results in a 43.2% probability of survival.

Table B

Number of survivors out of 100,000 born alive, by age, Hispanic origin and race, and sex: United States, 2023

Age | All origins | | | Hispanic | | | Non-Hispanic
Age | All origins | | | Hispanic | | | American Indian and Alaska Native | | | Asian | | | Black | | | White
Age | Total | Male | Female | Total | Male | Female | Total | Male | Female | Total | Male | Female | Total | Male | Female | Total | Male | Female
0 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000 | 100,000
1 | 99,441 | 99,398 | 99,487 | 99,497 | 99,459 | 99,536 | 99,088 | 98,977 | 99,210 | 99,657 | 99,623 | 99,693 | 98,913 | 98,850 | 98,978 | 99,554 | 99,513 | 99,597
5 | 99,332 | 99,275 | 99,392 | 99,406 | 99,354 | 99,463 | 98,839 | 98,696 | 98,997 | 99,591 | 99,551 | 99,634 | 98,706 | 98,641 | 98,798 | 99,470 | 99,397 | 99,539
10 | 99,271 | 99,208 | 99,336 | 99,356 | 99,299 | 99,419 | 98,742 | 98,616 | 98,883 | 99,550 | 99,510 | 99,593 | 98,587 | 98,519 | 98,698 | 99,415 | 99,333 | 99,495
15 | 99,188 | 99,110 | 99,269 | 99,285 | 99,220 | 99,356 | 98,556 | 98,387 | 98,742 | 99,498 | 99,453 | 99,546 | 98,433 | 98,340 | 98,590 | 99,342 | 99,240 | 99,442
20 | 98,901 | 98,705 | 99,108 | 99,017 | 98,846 | 99,200 | 97,886 | 97,620 | 98,156 | 99,343 | 99,292 | 99,455 | 97,853 | 97,464 | 98,315 | 99,109 | 98,921 | 99,299
25 | 98,428 | 98,024 | 98,851 | 98,563 | 98,185 | 98,970 | 96,715 | 96,211 | 97,210 | 99,090 | 98,991 | 99,346 | 96,956 | 96,141 | 97,855 | 98,713 | 98,368 | 99,070
30 | 97,810 | 97,145 | 98,505 | 97,946 | 97,242 | 98,695 | 94,892 | 93,929 | 95,867 | 98,838 | 98,648 | 99,220 | 95,940 | 94,710 | 97,265 | 98,156 | 97,593 | 98,742
35 | 96,989 | 96,020 | 97,999 | 97,206 | 96,155 | 98,332 | 92,247 | 90,563 | 93,986 | 98,570 | 98,283 | 99,083 | 94,680 | 92,996 | 96,468 | 97,358 | 96,524 | 98,226
40 | 95,981 | 94,685 | 97,333 | 96,366 | 94,967 | 97,876 | 89,079 | 86,564 | 91,694 | 98,252 | 97,842 | 98,880 | 93,100 | 90,888 | 95,407 | 96,338 | 95,191 | 97,534
45 | 94,708 | 93,061 | 96,427 | 95,361 | 93,587 | 97,283 | 85,481 | 82,351 | 88,750 | 97,786 | 97,198 | 98,574 | 91,068 | 88,280 | 93,928 | 95,045 | 93,565 | 96,591
50 | 93,113 | 91,067 | 95,245 | 94,106 | 91,966 | 96,434 | 81,002 | 76,885 | 85,327 | 97,143 | 96,300 | 98,153 | 88,589 | 85,148 | 92,066 | 93,409 | 91,563 | 95,344
55 | 90,901 | 88,365 | 93,545 | 92,424 | 89,850 | 95,226 | 75,798 | 70,836 | 81,058 | 96,142 | 94,988 | 97,430 | 85,379 | 81,159 | 89,606 | 91,128 | 88,824 | 93,552
60 | 87,684 | 84,464 | 91,038 | 89,987 | 86,784 | 93,471 | 69,963 | 64,209 | 76,089 | 94,702 | 93,045 | 96,420 | 80,897 | 75,746 | 86,037 | 87,833 | 84,868 | 90,956
65 | 83,102 | 79,011 | 87,354 | 86,439 | 82,433 | 90,766 | 63,341 | 56,587 | 70,564 | 92,560 | 90,197 | 94,880 | 74,723 | 68,390 | 81,029 | 83,194 | 79,406 | 87,183
70 | 76,999 | 71,877 | 82,295 | 81,701 | 76,659 | 87,034 | 56,224 | 48,569 | 64,425 | 89,172 | 85,961 | 92,213 | 66,815 | 59,188 | 74,367 | 77,066 | 72,290 | 82,078
75 | 68,957 | 62,860 | 75,228 | 74,971 | 68,837 | 81,314 | 48,308 | 40,410 | 56,887 | 84,070 | 79,712 | 88,058 | 57,437 | 48,742 | 65,967 | 68,936 | 63,207 | 74,913
80 | 57,812 | 51,062 | 64,735 | 65,597 | 58,690 | 72,570 | 39,563 | 32,338 | 47,491 | 76,147 | 70,719 | 81,048 | 46,475 | 37,429 | 55,311 | 57,515 | 51,126 | 64,156
85 | 42,699 | 35,847 | 49,655 | 52,031 | 44,658 | 59,039 | 29,228 | 23,470 | 35,539 | 63,115 | 56,634 | 68,817 | 33,379 | 25,005 | 41,478 | 42,089 | 35,562 | 48,797
90 | 24,974 | 19,252 | 30,673 | 34,438 | 27,677 | 40,107 | 19,113 | 15,169 | 23,189 | 43,688 | 37,054 | 49,236 | 19,810 | 13,486 | 25,861 | 24,180 | 18,762 | 29,671
95 | 9,645 | 6,432 | 12,715 | 16,325 | 11,725 | 19,165 | 10,323 | 8,230 | 12,034 | 20,998 | 16,112 | 24,460 | 8,615 | 5,074 | 11,865 | 8,946 | 5,948 | 11,840
100 | 1,989 | 1,069 | 2,826 | 4,619 | 2,804 | 5,166 | 4,358 | 3,598 | 4,576 | 5,474 | 3,615 | 6,398 | 2,395 | 1,142 | 3,467 | 1,701 | 888 | 2,447

NOTES: Life tables by Hispanic origin and race are based on death rates that have been adjusted for race and ethnicity misclassification on death certificates; see Technical Notes in this report. Hispanic people may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

### Explanation of the columns of the life table

Column 1. Age (between x and x + 1)—Shows the age interval between the two exact ages indicated. For instance, “20–21” means the 1-year interval between the 20th and 21st birthdays.

Column 2. Probability of dying (q_x_)—Shows the probability of dying between ages x and x + 1. For example, for males in the age interval 20–21 years, the probability of dying is 0.001175 (Table 2). This column forms the basis of the life table; all subsequent columns are calculated from it.

Column 3. Number surviving (l_x_)—Shows the number of people from the original hypothetical cohort of 100,000 live births who survive to the beginning of each age interval. The l_x _values are computed from the q_x_ values, which are successively applied to the remainder of the original 100,000 people still alive at the beginning of each age interval. Consequently, out of 100,000 female babies born alive, 99,487 will complete the first year of life and enter the second; 99,336 will reach age 10; 99,108 will reach age 20; and 49,655 will live to age 85 (Table 3).

Column 4. Number dying (d_x_)—Shows the number dying in each successive age interval out of the original 100,000 live births. For example, out of 100,000 males born alive, 602 will die in the first year of life; 116 between ages 20 and 21; and 1,069 after reaching age 100 (Table 2). Each figure in column 4 is the difference between two successive figures in column 3.

Column 5. Person-years lived (L_x_)—Shows the number of person-years lived by the hypothetical life table cohort within an age interval x to x + 1. Each figure in column 5 represents the total time (in years) lived between two indicated birthdays by all those reaching the earlier birthday. Consequently, the figure 98,647 for males in the age interval 20–21 is the total number of years lived between the 20th and 21st birthdays by the 98,705 males (column 3) who reached their 20th birthday out of 100,000 males born alive (Table 2).

Column 6. Total number of person-years lived (T_x_)—Shows the total number of person-years that would be lived after the beginning of the age interval x to x + 1 by the hypothetical life table cohort. For example, the figure 5,598,276 is the total number of years lived after reaching age 20 by the 98,705 males who reached that age (Table 2).

Column 7. Expectation of life (e_x_)—The expectation of life at any given age is the average number of years remaining to be lived by those surviving to that age, based on a given set of age-specific rates of dying. It is calculated by dividing the total person-years that would be lived beyond age x by the number of people who survived to that age interval (T_x _/l_x_). Consequently, the average remaining lifetime for males who reach age 20 is 56.7 years (5,598,276 divided by 98,705) (Table 2).

## Results

### Life expectancy in the United States

Tables 1–18 show complete life tables for 2023 by Hispanic origin and race and sex. Table A summarizes life expectancy by age, Hispanic origin and race, and sex. Life expectancy at birth for 2023 represents the average number of years that a group of infants would live if they were to experience throughout life the age-specific death rates prevailing in 2023. For 2023, life expectancy at birth was 78.4 years, increasing by 0.9 year from 77.5 in 2022 (Table 19).

Table 19

Estimated life expectancy at birth, in years, by Hispanic origin and race and sex: Death-registration states, 1900–1928, and United States, 1929–2023

[For selected years, life table values shown are estimates; see Technical Notes in this report. Beginning in 1970, excludes death of nonresidents of the United States; see Technical Notes]
Area and year | | | | | | | Non-Hispanic
Area and year | All races and origins | | | Hispanic^1^ | | | American Indian and Alaska Native^1^ | | | Asian^1^ | | | ^Black1,2^ | | | ^White1^
Area and year | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
United States^3^ | Single race^4^
2023^5^ | 78.4 | 75.8 | 81.1 | 81.3 | 78.5 | 84.0 | 70.1 | 66.7 | 73.5 | 85.2 | 83.2 | 87.1 | 74.0 | 70.3 | 77.6 | 78.4 | 76.0 | 80.9
2022^5^ | 77.5 | 74.8 | 80.2 | 80.0 | 77.0 | 82.8 | 67.8 | 64.5 | 71.3 | 84.4 | 82.3 | 86.3 | 72.8 | 69.1 | 76.5 | 77.5 | 75.1 | 80.1
2021^5^ | 76.4 | 73.5 | 79.3 | 77.8 | 74.6 | 81.1 | 65.6 | 62.2 | 69.2 | 83.5 | 81.2 | 85.6 | 71.2 | 67.6 | 75.0 | 76.7 | 74.0 | 79.5
2020^5^ | 77.0 | 74.2 | 79.9 | 77.9 | 74.6 | 81.3 | 67.1 | 63.8 | 70.7 | 83.6 | 81.1 | 85.9 | 71.5 | 67.8 | 75.4 | 77.4 | 74.8 | 80.1
2019^5^ | 78.8 | 76.3 | 81.4 | 81.9 | 79.1 | 84.4 | 71.8 | 68.6 | 75.0 | 85.6 | 83.5 | 87.4 | 74.8 | 71.3 | 78.1 | 78.8 | 76.3 | 81.3
^20185^ | 78.7 | ^76.2^ | ^81.2^ | ^81.8^ | ^79.1^ | ^84.3^ | ^---^ | ^---^ | ^---^ | ^---^ | ^---^ | ^---^ | ^74.7^ | ^71.3^ | ^78.0^ | ^78.6^ | ^76.2^ | ^81.1^
| Bridged race^4^
2020^5^ | … | … | … | … | … | … | --- | --- | --- | --- | --- | --- | 71.9 | 68.1 | 75.6 | 77.5 | 74.9 | 80.2
2019^5^ | … | … | … | … | … | … | --- | --- | --- | --- | --- | --- | 75.0 | 71.6 | 78.2 | 78.8 | 76.4 | 81.3
2018^5^ | … | … | … | … | … | … | --- | --- | --- | --- | --- | --- | 74.9 | 71.5 | 78.1 | 78.7 | 76.2 | 81.1
2017^5^ | 78.6 | 76.1 | 81.1 | 81.8 | 79.1 | 84.3 | --- | --- | --- | --- | --- | --- | 74.9 | 71.5 | 78.1 | 78.5 | 76.1 | 81.0
2016^5^ | 78.7 | 76.2 | 81.1 | 81.8 | 79.1 | 84.3 | --- | --- | --- | --- | --- | --- | 74.9 | 71.6 | 78.0 | 78.6 | 76.2 | 81.0
2015^5^ | 78.7 | 76.3 | 81.1 | 81.9 | 79.3 | 84.3 | --- | --- | --- | --- | --- | --- | 75.1 | 71.9 | 78.1 | 78.7 | 76.3 | 81.0
2014^5^ | 78.9 | 76.5 | 81.3 | 82.1 | 79.4 | 84.5 | --- | --- | --- | --- | --- | --- | 75.3 | 72.2 | 78.2 | 78.8 | 76.5 | 81.2
2013^5^ | 78.8 | 76.4 | 81.2 | 81.9 | 79.2 | 84.2 | --- | --- | --- | --- | --- | --- | 75.1 | 71.9 | 78.1 | 78.8 | 76.5 | 81.2
2012^5^ | 78.8 | 76.4 | 81.2 | 81.9 | 79.3 | 84.3 | --- | --- | --- | --- | --- | --- | 75.1 | 71.9 | 78.1 | 78.9 | 76.5 | 81.2
2011^5^ | 78.7 | 76.3 | 81.1 | 81.8 | 79.2 | 84.2 | --- | --- | --- | --- | --- | --- | 75.0 | 71.8 | 77.8 | 78.7 | 76.4 | 81.1
2010^5^ | 78.7 | 76.2 | 81.0 | 81.7 | 78.8 | 84.3 | --- | --- | --- | --- | --- | --- | 74.7 | 71.5 | 77.7 | 78.8 | 76.4 | 81.1
2009^5,6^ | 78.5 | 76.0 | 80.9 | 81.1 | 78.4 | 83.5 | --- | --- | --- | --- | --- | --- | 74.4 | 71.0 | 77.4 | 78.7 | 76.3 | 81.0
2008^5,6^ | 78.2 | 75.6 | 80.6 | 80.8 | 78.0 | 83.3 | --- | --- | --- | --- | --- | --- | 73.9 | 70.5 | 77.0 | 78.4 | 76.0 | 80.7
2007^5,6^ | 78.1 | 75.5 | 80.6 | 80.7 | 77.8 | 83.2 | --- | --- | --- | --- | --- | --- | 73.5 | 69.9 | 76.7 | 78.4 | 75.9 | 80.8
2006^5,6^ | 77.8 | 75.2 | 80.3 | 80.3 | 77.5 | 82.9 | --- | --- | --- | --- | --- | --- | 73.1 | 69.5 | 76.4 | 78.2 | 75.7 | 80.6
2005^5,6^ | 77.6 | 75.0 | 80.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
2004^5,6^ | 77.6 | 75.0 | 80.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
2003^5,6^ | 77.2 | 74.5 | 79.7 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
2002^5,6^ | 77.0 | 74.4 | 79.6 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
2001^5,6^ | 77.0 | 74.3 | 79.5 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
2000 | 76.8 | 74.1 | 79.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1999 | 76.7 | 73.9 | 79.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1998 | 76.7 | 73.8 | 79.5 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1997 | 76.5 | 73.6 | 79.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1996 | 76.1 | 73.1 | 79.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1995 | 75.8 | 72.5 | 78.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1994 | 75.7 | 72.4 | 79.0 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1993 | 75.5 | 72.2 | 78.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1992 | 75.8 | 72.3 | 79.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1991 | 75.5 | 72.0 | 78.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1990 | 75.4 | 71.8 | 78.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1989 | 75.1 | 71.7 | 78.5 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1988 | 74.9 | 71.4 | 78.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1987 | 74.9 | 71.4 | 78.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1986 | 74.7 | 71.2 | 78.2 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1985 | 74.7 | 71.1 | 78.2 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1984 | 74.7 | 71.1 | 78.2 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1983 | 74.6 | 71.0 | 78.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1982 | 74.5 | 70.8 | 78.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1981 | 74.1 | 70.4 | 77.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1980 | 73.7 | 70.0 | 77.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1979 | 73.9 | 70.0 | 77.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1978 | 73.5 | 69.6 | 77.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1977 | 73.3 | 69.5 | 77.2 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1976 | 72.9 | 69.1 | 76.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1975 | 72.6 | 68.8 | 76.6 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1974 | 72.0 | 68.2 | 75.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1973 | 71.4 | 67.6 | 75.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1972^7^ | 71.2 | 67.4 | 75.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1971 | 71.1 | 67.4 | 75.0 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1970 | 70.8 | 67.1 | 74.7 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1969 | 70.5 | 66.8 | 74.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1968 | 70.2 | 66.6 | 74.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1967 | 70.5 | 67.0 | 74.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1966 | 70.2 | 66.7 | 73.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1965 | 70.2 | 66.8 | 73.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1964 | 70.2 | 66.8 | 73.7 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1963^8^ | 69.9 | 66.6 | 73.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1962^8^ | 70.1 | 66.9 | 73.5 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1961 | 70.2 | 67.1 | 73.6 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1960 | 69.7 | 66.6 | 73.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1959 | 69.9 | 66.8 | 73.2 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1958 | 69.6 | 66.6 | 72.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1957 | 69.5 | 66.4 | 72.7 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1956 | 69.7 | 66.7 | 72.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1955 | 69.6 | 66.7 | 72.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1954 | 69.6 | 66.7 | 72.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1953 | 68.8 | 66.0 | 72.0 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1952 | 68.6 | 65.8 | 71.6 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1951 | 68.4 | 65.6 | 71.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1950 | 68.2 | 65.6 | 71.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1949 | 68.0 | 65.2 | 70.7 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1948 | 67.2 | 64.6 | 69.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1947 | 66.8 | 64.4 | 69.7 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1946 | 66.7 | 64.4 | 69.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1945 | 65.9 | 63.6 | 67.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1944 | 65.2 | 63.6 | 66.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1943 | 63.3 | 62.4 | 64.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1942 | 66.2 | 64.7 | 67.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1941 | 64.8 | 63.1 | 66.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1940 | 62.9 | 60.8 | 65.2 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1939 | 63.7 | 62.1 | 65.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1938 | 63.5 | 61.9 | 65.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1937 | 60.0 | 58.0 | 62.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1936 | 58.5 | 56.6 | 60.6 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1935 | 61.7 | 59.9 | 63.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1934 | 61.1 | 59.3 | 63.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1933 | 63.3 | 61.7 | 65.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1932 | 62.1 | 61.0 | 63.5 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1931 | 61.1 | 59.4 | 63.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1930 | 59.7 | 58.1 | 61.6 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1929 | 57.1 | 55.8 | 58.7 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
Death-registration states | Bridged race^4—Con.^
1928 | 56.8 | 55.6 | 58.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1927 | 60.4 | 59.0 | 62.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1926 | 56.7 | 55.5 | 58.0 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1925 | 59.0 | 57.6 | 60.6 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1924 | 59.7 | 58.1 | 61.5 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1923 | 57.2 | 56.1 | 58.5 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1922 | 59.6 | 58.4 | 61.0 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1921 | 60.8 | 60.0 | 61.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1920 | 54.1 | 53.6 | 54.6 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1919 | 54.7 | 53.5 | 56.0 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1918 | 39.1 | 36.6 | 42.2 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1917 | 50.9 | 48.4 | 54.0 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1916 | 51.7 | 49.6 | 54.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1915 | 54.5 | 52.5 | 56.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1914 | 54.2 | 52.0 | 56.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1913 | 52.5 | 50.3 | 55.0 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1912 | 53.5 | 51.5 | 55.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1911 | 52.6 | 50.9 | 54.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1910 | 50.0 | 48.4 | 51.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1909 | 52.1 | 50.5 | 53.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1908 | 51.1 | 49.5 | 52.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1907 | 47.6 | 45.6 | 49.9 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1906 | 48.7 | 46.9 | 50.8 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1905 | 48.7 | 47.3 | 50.2 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1904 | 47.6 | 46.2 | 49.1 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1903 | 50.5 | 49.1 | 52.0 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1902 | 51.5 | 49.8 | 53.4 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1901 | 49.1 | 47.6 | 50.6 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
1900 | 47.3 | 46.3 | 48.3 | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---

--- Data not available.

… Category not applicable.^1^Life tables are based on death rates that have been adjusted for race and Hispanic-origin misclassification on death certificates; see Technical Notes.^2^Before 1970, data for the Black population are not available. Data shown for 1900–1969 are for the non-White population. See Technical Notes.^3^Includes Alaska in 1959 and Hawaii in 1960.^4^Life expectancies by single-race categories are not completely comparable with life expectancies by bridged-race categories and should be interpreted accounting for the change from bridged- to single-race categories. ^5^Life expectancies for 2001–2023 were calculated using a revised methodology described in Technical Notes.^6^Life expectancies for 2001–2009 have been re-estimated using new intercensal population estimates and may differ from data previously published; see Technical Notes.^7^Deaths based on a 50% sample.^8^Figures by race exclude data for residents of New Jersey; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

The difference in life expectancy between the sexes was 5.3 years in 2023, decreasing 0.1 year from 2022. From 1900 to 1975, the difference in life expectancy between the sexes increased from 2.0 years to 7.8 years (Figure 1, Table 19). The increasing gap during these years is attributed to increases in male mortality due to ischemic heart disease and lung cancer, both of which increased largely as the result of men’s early and widespread adoption of cigarette smoking (11,12). Between 1979 and 2010, the difference in life expectancy between the sexes narrowed from 7.8 years to 4.8 years, increased to 5.8 in 2021, and then declined to 5.3 in 2023 (Figure 1, Table 19).

Figure 1 Life expectancy at birth, by sex: United States, 1900–2023

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 1 is a line graph showing life expectancy at birth by sex from 1900 through 2023.

The 2023 life table may be used to compare life expectancy at any age from birth onward. Based on mortality experienced in 2023, a person age 65 could expect to live an average of 19.5 more years for a total of 84.5 years; a person age 85 could expect to live an additional 6.7 years for a total of 91.7 years; and a person age 100 could expect to live an additional 2.2 years, on average (Table A).

### Life expectancy by Hispanic origin and race

In 2023, the Hispanic population had a life expectancy of 81.3 years. Within the non-Hispanic population, the Asian population had the highest life expectancy at birth (85.2 years), followed by the White (78.4), Black (74.0), and American Indian and Alaska Native (70.1) populations (Table A, Figure 2). From 2022 to 2023, life expectancy at birth increased for all Hispanic-origin and race populations (Figure 2). Life expectancy increased by 1.3 years for the Hispanic population (80.0 to 81.3) (Table 19). Within the non-Hispanic population, life expectancy increased by 2.3 years for the American Indian and Alaska Native population (67.8 to 70.1), 1.2 years for the Black population (72.8 to 74.0), 0.9 year for the White population (77.5 to 78.4), and 0.8 year for the Asian population (84.4 to 85.2).

Figure 2 Life expectancy at birth, by Hispanic origin and race: United States, 2019–2023

NOTE: People of Hispanic origin may be of any race. SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 2 is a bar graph showing life expectancy at birth by Hispanic origin and race in 2019, 2020, 2021, 2022, and 2023.

From 2022 to 2023, life expectancy increased by 1.5 years for Hispanic males (77.0 to 78.5) and by 1.2 years for Hispanic females (82.8 to 84.0) (Figure 3). Within the non-Hispanic population, American Indian and Alaska Native males and females experienced the greatest increase in life expectancy, 2.2 years each (64.5 to 66.7, and 71.3 to 73.5, respectively). Black males and Black females experienced increases of 1.2 years (69.1 to 70.3) and 1.1 years (76.5 to 77.6), respectively. Asian males and White males both experienced an increase of 0.9 year (82.3 to 83.2 and 75.1 to 76.0, respectively). Asian females and White females each experienced an increase of 0.8 year (86.3 to 87.1 and 80.1 to 80.9, respectively) (Figure 3).

Figure 3 Change in life expectancy at birth, by Hispanic origin and race and sex: United States, 2022–2023

NOTES: Life tables by Hispanic origin and race are based on death rates that have been adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes in this report. People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 3 is a bar graph showing change in life expectancy at birth from 2022 to 2023 by Hispanic origin and race and sex.

### Effect on life expectancy of changes in cause-specific mortality

Changes in mortality by age and cause of death can have a major effect on life expectancy (Figures 4–6). Declines in cause-specific mortality contribute to increases in life expectancy, while increases in cause-specific mortality contribute to decreases in life expectancy. The increase of 0.9 year in life expectancy between 2022 and 2023 was primarily due to decreases in mortality due to COVID-19 (51.9% of the positive contribution), heart disease (13.1%), unintentional injuries (5.9%), cancer (3.5%), and diabetes (3.3%). The increase in life expectancy would have been even greater were it not for the offsetting effects of increases in mortality due to nutritional deficiencies (78.3%), Parkinson disease (12.6%), whooping cough (3.9%), meningococcal infection (3.0%), and malaria (1.1%) (see Technical Notes for a description of the life table partitioning method) (13).

Figure 4 Percent contribution to the changes in life expectancy from 2022 to 2023, by cause of death and Hispanic origin and race: Total and American Indian and Alaska Native, non-Hispanic populations

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 4 is a bar graph showing the percent contribution to changes in life expectancy from 2022 to 2023 by cause of death for the total and American Indian and Alaska Native non-Hispanic populations.

The American Indian and Alaska Native non-Hispanic population experienced the largest increase in life expectancy between 2022 and 2023 (2.3 years) (Table 19). The increase was primarily due to decreases in mortality due to COVID-19 (41.9%), chronic liver disease and cirrhosis (12.4%), heart disease (5.7%), diabetes (5.6%), and unintentional injuries (5.4%) (Figure 4). The increase in life expectancy would have been greater were it not for the offsetting effects of increases in mortality due to aortic aneurysm (39.6%), Infections of kidney (13.9%), Enterocolitis due to Clostridium difficile (9.9%), pneumonitis (9.5%), and meningitis (1.8%).

The second greatest increase in life expectancy was experienced by the Hispanic population (1.3 years), primarily because of decreases in mortality due to COVID-19 (56.9%), heart disease (12.0%), cancer (4.7%), diabetes (3.6%), and Alzheimer disease (3.1%) (Figure 6). The increase in life expectancy would have been greater were it not for the offsetting effects of increases in mortality due to perinatal conditions (58.1%), suicide (17.8%), nutritional deficiencies (7.0%), Diseases of appendix (5.5%), and pneumonitis (5.4%).

Figure 6 Percent contribution to the changes in life expectancy from 2022 to 2023, by cause of death and Hispanic origin and race: Asian, non-Hispanic and Hispanic populations

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 6 is a bar graph showing the percent contribution to changes in life expectancy from 2022 to 2023 by cause of death for the Asian non-Hispanic and Hispanic populations.

The third greatest increase in life expectancy was experienced by the Black non-Hispanic population (1.2 years). The increase was due primarily to decreases in mortality due to COVID-19 (48.3%), heart disease (14.1%), homicide (7.2%), diabetes (5.0%), and cancer (4.4%) (Figure 5). The increase in life expectancy was offset by increases in mortality due to suicide (33.8%), congenital malformations (22.5%), nutritional deficiencies (20.2%), aortic aneurysm (16.0%), and hernia (2.2%).

The fourth largest increase in life expectancy was experienced by the White non-Hispanic population (0.9 year). The increase was primarily due to decreases in mortality due to COVID-19 (50.0%), heart disease (12.7%), unintentional injuries (10.7%), diabetes (3.0%), and cancer (2.9%) (Figure 5). The increase in life expectancy would have been greater were it not for the offsetting effects of increases in mortality due to nutritional deficiencies (66.8%), Parkinson disease (18.1%), meningococcal infection (5.3%), whooping cough (4.0%), and tuberculosis (1.6%).

Figure 5 Percent contribution to the changes in life expectancy from 2022 to 2023, by cause of death and Hispanic origin and race: White, non-Hispanic and Black, non-Hispanic populations

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 5 is a bar graph showing the percent contribution to changes in life expectancy from 2022 to 2023 by cause of death for the White and Black non-Hispanic populations.

The Asian non-Hispanic population experienced the smallest increase in life expectancy (0.8 year). The increase was primarily because of decreases in mortality due to COVID-19 (50.9%), heart disease (18.3%), cancer (8.9%), stroke (6.4%), and Alzheimer disease (2.3%). The increase in life expectancy was offset by increases in mortality due to congenital malformations (24.9%), influenza and pneumonia (17.9%), septicemia (16.1%), nutritional deficiencies (14.6%), and homicide (6.0%).

### Survivorship in the United States

Table B summarizes the number of survivors out of 100,000 people born alive (l_x_) by age, Hispanic origin and race, and sex for 2023. In 2023, 99.4% of all infants born in the United States survived the first year of life; 98.9% survived to age 20; 83.1% survived to age 65; 42.7% survived to age 85; and 2.0% survived to age 100.

### Survivorship by Hispanic origin and race

In 2023, 99.5% of Hispanic infants survived the first year of life. Among the non-Hispanic population, 99.7% of Asian, 99.6% of White, 99.1% of American Indian and Alaska Native, and 98.9% of Black infants survived the first year of life (Figure 7, Table B). The probability of survival by select ages varied across the Hispanic-origin and race groups. In 2023, 99.0% of the Hispanic population survived to age 20, 86.4% to age 65, and 52.0% to age 85. Among the non-Hispanic population, the Asian population had the highest survival probability at age 20 (99.3%), followed by the White population (99.1%), the Black population (97.9%), and the American Indian and Alaska Native population (97.9%). By age 65, the Asian population had the highest survival probability at 92.6%, followed by the White (83.2%), Black (74.7%), and American Indian and Alaska Native (63.3%) populations. The survival advantage experienced by the Asian population increased with age so that by age 85, 63.1% had survived, compared with 42.1% of the White, 33.4% of the Black, and 29.2% of the American Indian and Alaska Native populations.

Figure 7 Percentage surviving, by Hispanic origin and race, age, and sex: United States, 2023 NOTE: People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 7 is a line graph showing the percent surviving by Hispanic origin and race, age and sex in 2023.

## Summary

U.S. life expectancy at birth increased for the second year in a row following 2 years of decline between 2019 and 2021 that resulted mainly from the COVID-19 pandemic. Increases in life expectancy between 2022 and 2023 occurred across all racial, ethnic, and sex groups. However, the increases in life expectancy in 2022 and 2023 combined were not enough to make up for the losses in life expectancy between 2019 and 2021. Life expectancy at birth in 2023 was 0.4 year lower for the total population, 0.5 year lower for males, and 0.3 year lower for females than in 2019.

The American Indian and Alaska Native non-Hispanic population experienced the largest increases in life expectancy between 2022 and 2023 (2.3 years), but life expectancy remained 1.7 years lower than it was in 2019. Similarly, the Hispanic population experienced a life expectancy increase of 1.3 years between 2022 and 2023, but its life expectancy remained 0.6 year lower than it was in 2019. The Black non-Hispanic population gained 1.2 years in life expectancy between 2022 and 2023 but remained 0.8 year below what had been attained in 2019. The White non-Hispanic and Asian non-Hispanic populations gained 0.9 year and 0.8 year in life expectancy between 2022 and 2023, respectively, but life expectancy remained 0.4 year below what each had attained in 2019.

## Technical Notes

### The U.S. life table program

The National Center for Health Statistics prepares complete period life tables for the U.S. population annually. Annual final life tables are based on a complete count of all reported deaths and postcensal population estimates. Beginning with the first decennial census (1900) through the 2010 census, decennial life tables were produced for every decade. These were complete period life tables based on decennial census data and final deaths for a 3-year period around the census year. Between 1900 and 1945, the decennial series was the only set of official life tables produced. This series also included state-level complete life tables for the decennial periods 1939–1941 to 1999–2001. The decennial life tables series was discontinued due to the development of new methodologies that improved estimation of mortality at the older ages in the annual life tables series and the addition of an annual series of complete state-level life tables (14). The annual complete state-level life tables series started with data year 2018 (15).

Available since 1945, the annual life tables are based on deaths occurring during the calendar year and on midyear postcensal population estimates provided by the U.S. Census Bureau. From 1945 to 1996, the annual life tables were abridged life tables, closed at age 85 and older, and were constructed by reference to a standard table (4). Beginning with 1997 mortality data, the annual abridged life tables were replaced with complete life tables expanded to ages 100 and older based on a methodology similar to that of the 1989–1991 decennial life tables. The methodology was revised for data years 2000–2007 using a methodology similar to that of the 1999–2001 decennial life tables (16). Beginning with data year 2008, the life table methodology was revised with a new smoothing technique applied to death rates in the oldest ages (17).

The methodology used to estimate the 2008–2023 life tables is different from that used to estimate the 2000–2007 life tables with respect to the technique used to estimate the probabilities of death for ages older than 65. The methodology used to produce the life tables for 2008–2023 does not model the probabilities of death beginning at age 66, as was done for data years 2000–2007, but rather at ages above 85 or so (the exact ages at which smoothing techniques are used depends on the specific racial and ethnic population). Research into the methodology developed and used for the 1999–2001 decennial life tables and applied to the annual life tables has revealed that it is not necessary to model (or smooth) the probabilities of death beginning at age 66. The observed blended vital statistics and Medicare data for ages 66–85 are robust enough and do not require additional smoothing (16). A full description of the methodology used to estimate the 2023 life tables is provided below. See “United States Life Tables, 2005” (16) for a detailed description of the methodology used for data years 2000–2007.

Beginning with 2006 mortality data, life tables by Hispanic origin and race, including Hispanic (regardless of race), Black non-Hispanic and White non-Hispanic were added to the annual life table program. Before this time, concerns over data limitations such as racial and ethnic misclassification on U.S. death certificates and lack of Medicare data for older populations other than the White and Black populations (regardless of Hispanic origin), prevented the estimation of life tables for the Hispanic-origin population. Research that identified and quantified these data limitations resulted in reliable methodological strategies to address these data problems (8–10,17). Beginning with 2019 mortality data, the annual life table program was expanded to include the American Indian and Alaska Native non-Hispanic and Asian non-Hispanic populations.

### Revised intercensal life table values

Life table values for 1960–1969, 1970–1979, and 1980–1989 were constructed using the U.S. decennial life tables for 1959–1961, 1969–1971, and 1979–1981, respectively, as the standard tables. The life table values for years before 1989 appearing in this report are based on revised intercensal estimates of the populations for those years. As a result, the life table values for these years may differ from the life table values for those years published in Vital Statistics of the United States for 1989 and earlier years (https://www.cdc.gov/nchs/products/vsus.htm).

Life table values for 1991–1999 presented in this report are based on postcensal population estimates enumerated in the 1990 decennial census. Life table values for 2001–2009 presented in this report are based on revised intercensal population estimates based on the 2010 decennial census and the revised methodology used to estimate the 2008–2023 life tables. As a result, the values may differ from those previously published in annual final mortality and life table reports. The revised intercensal life tables for 2001–2009 can be accessed by links provided under each of the annual life table reports in: https://www.cdc.gov/nchs/products/life_tables.htm.

#### Geographic coverage

The geographic areas covered in life tables before 1929–1931 were limited to death-registration areas. Life tables for 1900–1902 and 1909–1911 were constructed using mortality data from the 1900 death-registration states (10 states and the District of Columbia), and tables for 1919–1921 used mortality data from the 1920 death-registration states (34 states and the District of Columbia). The tables for 1929–1931 through 1958 cover the coterminous United States. Decennial life table values for the 3-year period 1959–1961 were calculated from data that include both Alaska and Hawaii for each year. Data for each year shown in Table 19 include Alaska beginning in 1959 and Hawaii beginning in 1960. However, the inclusion of these two states does not materially affect life table values.

#### New Jersey data, 1962–1964

The life tables for 1962 and 1963 for the six population groups involving race (White and Black, regardless of Hispanic origin) do not include data from New Jersey, which omitted the item on race from its certificates of live birth, death, and fetal death in use at the beginning of 1962. The item was restored during the latter part of 1962. However, the certificate revision without this item was used for most of 1962, as well as for 1963. For computing vital rates, populations by age, race, and sex (excluding New Jersey) were estimated to obtain comparable denominators. About 7% of the New Jersey death records for 1964 did not contain the race designation. When the records were being electronically processed for this state, the “race not stated” deaths were allocated proportionally to either White or Black (regardless of Hispanic origin).

#### Nonresidents

Beginning in 1970, the deaths of nonresidents of the United States have been excluded from the life table statistics.

### Data for calculating life table functions

The data used to prepare the U.S. life tables include final death counts from the National Vital Statistics System, population estimates from the U.S. Census Bureau, and death and population counts for Medicare beneficiaries ages 66–99 from the Centers for Medicare & Medicaid Services.

#### Vital statistics data

Death counts used for computing the life tables presented in this report are final numbers of deaths for 2023 collected from death certificates filed in state vital statistics offices and reported to the National Center for Health Statistics as part of the National Vital Statistics System. Hispanic origin and race are reported separately on the death certificate.

Beginning with the 2018 data year, all 50 states and the District of Columbia reported deaths based on the 2003 revision of the U.S. Standard Certificate of Death for the entire year (18). The revision is based on the 1997 Office of Management and Budget standards (5). The 1997 standards allow people to report more than one race and increased the race choices from four to five by separating the Asian and Pacific Islander groups. The Hispanic category did not change, remaining consistent with previous reports.

The Hispanic-origin and race groups in this report follow the 1997 standards and differ from the race categories used in previous reports. The new categories are Hispanic, American Indian and Alaska Native non-Hispanic single race, Asian non-Hispanic single race, Black non-Hispanic single race, and White non-Hispanic single race. From 2003 through 2017, some deaths were reported using the 1989 certificate revision that allowed the reporting of only one race (6). During those years, multiple-race data were bridged to single-race categories. Use of the bridged-race process was discontinued in 2018 when all states collected data on race according to 1997 Office of Management and Budget guidelines for the full data year. The Hispanic-origin category was not affected by the revised standards.

#### Census population data

The population data used to estimate the life tables shown in this report are postcensal population estimates based on the blended base created by the U.S. Census Bureau to produce post-2020 census population estimates. The blended base consists of the blend of Vintage 2020 postcensal population estimates, based on the April 1, 2010, decennial census; 2020 Demographic Analysis Estimates; and 2020 Census Edited File (CEF) (https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2023/methods-statement-v2023.pdf).

To produce death rates for 2000–2017, the reported population data for multiple-race people had to be bridged back to single-race categories. Additionally, the 2010 census counts were modified for consistency with the 1977 Office of Management and Budget race categories, that is, to report the data for Asian and Native Hawaiian or Other Pacific Islander people as a combined category (Asian or Pacific Islander) and to reflect age as of the census reference date (6). The procedures used to produce the bridged-race populations are described elsewhere (19).

#### Medicare data

Medicare data are considered more accurate than vital statistics and census data at the oldest ages because Medicare enrollees must have proof of age in order to enroll (20,21). However, the reliability of Medicare data beyond age 100 declines because of the small percentage of people who enrolled in the early years of the Medicare program and for whom it was not possible to verify exact age (20,21). Further, the Medicare race and ethnicity classification system makes it impossible to correctly identify the Hispanic (irrespective of race), American Indian and Alaska Native, Asian, or Native Hawaiian and Other Pacific Islander populations (regardless of Hispanic origin) (21). It is, however, possible to use Medicare data to estimate old-age mortality for both the White and Black race groups, irrespective of Hispanic origin, as has been done traditionally, and to estimate old-age mortality for the non-Hispanic segments of these two populations (14). As a result, data from the Medicare program are used to supplement vital statistics and census data for ages 66–99 for the total population and the Black non-Hispanic and White non-Hispanic populations presented in this report (14).

To estimate death rates for the Medicare total, Black non-Hispanic, and White non-Hispanic populations in 2023, age-specific numbers of deaths and population counts by sex and race for the population ages 66–99 from the 2023 Medicare file were used. The data file is created by CMS for the Social Security Administration, which shares the data with National Center for Health Statistics under a special agreement. The 2023 file contains 2023 midyear Medicare population counts (June 30, 2023) and calendar-year Medicare death counts (January 1 through December 31, 2023). Age for both deaths and midyear population counts is calculated as age at last birthday.

### Preliminary adjustment of the data

#### Adjustments for unknown age

An adjustment is made to account for the small proportion of deaths each year for which age is not reported on the death certificate. The number of deaths in each age category is adjusted proportionally to account for those with not-stated ages. The following factor (F) is used to make the adjustment. F is calculated for the total and for each sex group within a racial and ethnic population for which life tables are constructed:

F = (D)/(D^a^) Factor F equals the total number of deaths divided by the number of deaths for which age is stated. [1]

where D is the total number of deaths and D^a^ is the total number of deaths for which age is stated. F is then applied by multiplying it by the number of deaths in each age group. Table I shows values for F by sex used to adjust mortality data for the total, Hispanic, American Indian and Alaska Native non-Hispanic, Asian non-Hispanic, Black non-Hispanic, and White non-Hispanic populations in 2023.

Table I

Values for F used to adjust for not-stated age based on 2023 mortality data

Hispanic origin and race and sex | Total deaths | Total deaths for which age was not stated | F
Total | 3,090,964 | 80 | 1.00002588
Male | 1,617,085 | 55 | 1.00003401
Female | 1,473,879 | 25 | 1.00001696
Hispanic | 258,896 | 3 | 1.00001159
Male | 145,835 | 2 | 1.00001371
Female | 113,061 | 1 | 1.00000884
Non-Hispanic:
American Indian and Alaska Native | 21,274 | – | 1.00000000
Male | 11,600 | 1 | 1.00008621
Female | 9,674 | – | 1.00000000
Asian | 85,769 | – | 1.00000000
Male | 43,922 | – | 1.00000000
Female | 41,847 | 1 | 1.00002390
Black | 385,399 | 5 | 1.00001297
Male | 205,891 | 3 | 1.00001457
Female | 179,508 | 2 | 1.00001114
White | 2,308,328 | 39 | 1.00001690
Male | 1,191,617 | 13 | 1.00001091
Female | 1,116,711 | 9 | 1.00000806

– Quantity zero.

NOTE: Hispanic people may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

#### Adjustment for misclassification of Hispanic origin and race on death certificates

Two data sources were used to adjust for Hispanic-origin and race misclassification on death certificates. For the Hispanic, Asian non-Hispanic, Black non-Hispanic, and White non-Hispanic populations, the National Longitudinal Mortality Study (NLMS) was used to produce classification ratios (or correction factors) to adjust observed sex and age-specific death rates for misclassification on death certificates (8). The NLMS consists of a series of Current Population Surveys (CPS) (1979–2011) linked to vital statistics mortality data through the National Death Index (NDI) (8). For the American Indian and Alaska Native non-Hispanic population, an extract of the 2010 CEF–Census Unedited File (CUF) Match File containing records for people classified by race as American Indian and Alaska Native alone or in combination with another race in the 2010 decennial census was linked to NDI to identify decedents for the period April 1, 2010, to December 31, 2011. The resulting 34,366 CEF–CUF Match American Indian and Alaska Native Extract—Mortality Linked Data decedent records were used to estimate classification ratios to correct for race and Hispanic-origin misclassification on death certificates for the American Indian and Alaska Native non-Hispanic population (10).

The classification ratios consist of a comparison of self-reported Hispanic origin and race on Current Population Surveys or the decennial census, with Hispanic origin and race reported on the death certificates of the samples of decedents in the National Longitudinal Mortality Study who died during 1999–2011 and decedents in the Census Edited File–Census Unedited File Match American Indian and Alaska Native Extract who died between April 1, 2010, and December 31, 2011 (8,10). Linked records are used to estimate sex-age-specific ratios of survey or census Hispanic-origin and race counts to death certificate counts (8,10).

The survey or census death certificate ratio, or “classification ratio,” is the ratio of the count (weighted in the case of Current Population Surveys) of self-reported race and ethnicity on the survey or census to the count (weighted in the case of Current Population Surveys) of the same racial or ethnic category on the death certificates of the sample of the National Longitudinal Mortality Study (Census Edited File–Census Unedited File Match American Indian and Alaska Native Extract) decedents described previously. It can be interpreted as the net difference in assignment of a specific Hispanic-origin and race category between the two classification systems and can be used as a correction factor for Hispanic-origin and race misclassification (8,10). It is assumed that the race and ethnicity reported by a survey or census respondent is more reliable than proxy reporting of race and ethnicity by a funeral director who has little personal knowledge of the decedent. Also, the 1997 Office of Management and Budget standards mandate that self-identification should be the standard used for the collection and recording of race and ethnicity information (5).

Classification ratios discussed previously are used to adjust the age-specific number of deaths for ages 1–95 and older for the total Hispanic, American Indian and Alaska Native non-Hispanic, Asian non-Hispanic, Black non-Hispanic, and White non-Hispanic populations, and by sex for each group, as follows:

n D_x_ =_n_ D_x_ F *_n_ C R_x_ Final age-specific counts of death equal age-specific number of deaths adjusted for unknown age multiplied by age-specific classification ratios used to correct for the misclassification of race and Hispanic origin on death certificates. [2]

where _n_D_x_^F^ is the age-specific number of deaths adjusted for unknown age as described previously, _n_CR_x_ are the sex- and age-specific classification ratios used to correct for the misclassification of Hispanic origin and race on death certificates, and _n_D_x_ are the final age-specific counts of death adjusted for age and Hispanic-origin and race misclassification. Table II shows values of the sex- and age-specific classification ratios, _n_CR_x_, by Hispanic origin and race.

Table II

Classification ratios, by Hispanic origin and race, age, and sex

Age (years) | Hispanic^1^ | | | Non-Hispanic
Age (years) | Hispanic^1^ | | | American Indian and Alaska Native^1^ | | | Asian^1,2^ | | | Black^1^ | | | White^1^
Age (years) | Total | Male | Female | Total | Male | Female | Total | Male | Female | Total | Male | Female | Total | Male | Female
All ages | 1.0329 | 1.0362 | 1.0294 | 1.3354 | 1.3488 | 1.3197 | 1.0331 | 1.0480 | 1.0117 | 1.0047 | 1.0041 | 1.0053 | 0.9995 | 0.9993 | 0.9997
0^3^ | 1.0563 | 1.0956 | 1.0203 | 0.9069 | 0.9075 | 0.9243 | 0.7883 | 0.8401 | 0.7423 | 1.0292 | 1.0729 | 0.9859 | 0.9595 | 1.0128 | 0.9080
1–14 | 0.9905 | 0.9659 | *1.0299 | 1.1243 | 1.1546 | 1.0833 | *0.8655 | *0.8426 | *1.0000 | 1.0266 | 0.9379 | *1.1751 | 0.9918 | 1.0755 | 0.8770
15–24 | 0.9668 | 0.9325 | 1.0604 | 1.1462 | 1.1201 | 1.2190 | 1.2285 | *1.4276 | *0.9721 | 1.0248 | 1.0215 | 1.0343 | 0.9976 | 1.0019 | 0.9869
25–34 | 1.0354 | 1.0401 | 1.0232 | 1.1375 | 1.1557 | 1.1033 | 1.1527 | 1.0967 | *1.2648 | 0.9855 | 0.9770 | 1.0008 | 1.0021 | 1.0034 | 0.9994
35–44 | 1.0434 | 1.0645 | 1.0066 | 1.1799 | 1.1815 | 1.1772 | 1.0338 | 1.0459 | 1.0125 | 1.0062 | 1.0073 | 1.0048 | 0.9980 | 0.9997 | 0.9951
45–54 | 1.0584 | 1.0372 | 1.0953 | 1.3915 | 1.3913 | 1.3916 | 1.0699 | 1.1123 | 1.0113 | 1.0002 | 1.0019 | 0.9982 | 0.9969 | 0.9965 | 0.9976
55–64 | 1.0571 | 1.0517 | 1.0659 | 1.4281 | 1.4547 | 1.3917 | 1.0274 | 1.0694 | 0.9784 | 1.0003 | 0.9965 | 1.0046 | 0.9994 | 0.9992 | 0.9997
65–74 | 1.0295 | 1.0485 | 1.0072 | 1.3654 | 1.4244 | 1.2980 | 1.0845 | 1.0841 | 1.0850 | 1.0062 | 1.0055 | 1.0070 | 0.9967 | 0.9967 | 0.9966
75–84 | 1.0192 | 1.0188 | 1.0196 | 1.3099 | 1.3367 | 1.2852 | 1.0305 | 1.0328 | 1.0281 | 1.0057 | 1.0057 | 1.0058 | 1.0004 | 1.0003 | 1.0004
85–94 | 1.0208 | 1.0313 | 1.0137 | 1.3845 | 1.3807 | 1.3870 | 0.9962 | 0.9983 | 0.9944 | 1.0110 | 1.0155 | 1.0086 | 1.0008 | 1.0007 | 1.0009
95 and over | 1.0732 | 1.0509 | 1.0842 | 1.3951 | 1.3043 | 1.4240 | 0.9755 | 1.0238 | 0.9405 | 0.9980 | 0.9872 | 0.9954 | 1.0005 | 0.9995 | 1.0008

* Ratio does not meet National Center for Health Statistics standards of reliability because either the unweighted number of Current Population Survey deaths, the unweighted number of death certificate deaths, or both are based on fewer than 20 deaths.

^1^Classification ratios for the Hispanic, Asian non-Hispanic, Black non-Hispanic, and White non-Hispanic populations are based on the National Longitudinal Mortality Study data (see https://www.cdc.gov/nchs/data/series/sr_02/sr02_172.pdf). Classification ratios for the American Indian and Alaska Native non-Hispanic population are based on the census American Indian and Alaska Native-Extract Mortality Linked Data (see https://www.cdc.gov/nchs/data/nvsr/nvsr70/NVSR70-12.pdf).

^2^Classification ratios for the Asian non-Hispanic population were estimated based on data for the Asian non-Hispanic and Pacific Islander non-Hispanic populations combined due to data availability. However, the ratios reflect misclassification predominantly among the Asian non-Hispanic population because it makes up more than 95% of the Asian non-Hispanic and Pacific Islander non-Hispanic populations combined.

^3^Ratios for age 0 are estimated as the ratio of infant mortality rates based on the traditional death and birth files to the infant mortality rates based on the 2023 linked birth/infant death data file. They are only shown for illustrative purposes; see report text for details.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Because classification ratios for infant deaths are unreliable due to small sample sizes or counts, corrections for racial and ethnic misclassification of infant deaths are addressed by using infant death counts and live birth counts from the 2022 and 2023 linked birth/infant death data files rather than the traditional birth and death data files (22,23). In the linked file, each infant death record is linked to its corresponding birth record so that the race and ethnicity of the mother reported on the birth record can be ascribed to the infant death record. As a result, race- and ethnicity-specific infant mortality rates estimated with the linked file do not have racial and ethnic discrepancies between the numerator and denominator of the rate. A ratio of infant mortality rates based on the traditional birth and death data files to infant mortality rates based on the linked birth/infant death data file shows that using the traditional files overestimates the infant mortality rate by 5.6% for Hispanic, and 2.9% for Black non-Hispanic infants; and underestimates the infant mortality rate by 21.2% for Asian non-Hispanic, 9.3% for American Indian and Alaska Native non-Hispanic, and 4.1% for White non-Hispanic infants (see ratios for age 0 in Table II). Because the probability of death at age 0 used to calculate the life table uses live births in the denominator (procedure described in “Calculation of q_x_ at age 0”), it is preferable to use the linked birth/infant death data file.

#### Interpolation of P_x_ and D_x_

Anomalies—both random and those associated with reporting age at death—can be problematic when using vital statistics and census data by single years of age to estimate the probability of death (1,3). Graduation techniques are often used to eliminate these anomalies and to derive a smooth curve by age. Beers’ ordinary minimized fifth difference formula is used to obtain smoothed values of population counts (P_x_) and death counts (D_x_) from 5-year age groupings of _n_P_x _ from age 0 to 99 and _n_D_x_ from age 5 to 99, and where _n_D_x_ has first been adjusted for not-reported age and Hispanic-origin and race misclassification on the death certificate (see reference 24 for details on the application of Beers’ method).

### Calculation of the probability of dying (q_x_)

The first step in calculating a complete period life table is the estimation of the age-specific probability of dying, q_x_, which is derived from the age-specific death rate, m_x_ (3,16). In the life table cohort,

m_x_ = (d_x_)/(L_x_) The age-specific death rate equals the number of deaths occurring between ages x and x plus one divided by the number of person-years lived by the life table cohort between ages x and x plus one.

where d_x_ is the number of deaths occurring between ages x and x + 1, and L_x_ is the number of person-years lived by the life table cohort between ages x and x + 1. The conversion of the age-specific death rate, m_x_, to the age-specific probability of death, q_x_, is as follows:

q_x_ = (m_x_)/(1 + (1 − a_x_) m_x_) The age-specific probability of death equals the age-specific death rate divided by one plus one minus the number of person-years lived in the age interval multiplied by the age-specific death rate. [3]

where a_x_ is the fraction of the number of person-years lived in the age interval by members of the life table cohort who died in the interval. When the age interval is 1 year, except at infancy, a_x _= 1/2; in other words, deaths occur on average midway through the age interval. As a result,

q_x_ = (m_x_)/(1 + (1)/(2) m_x_) The age-specific probability of death equals the age-specific death rate divided by one plus one-half multiplied by the age-specific death rate. [4]

Because the complete period life table is based on the age-specific death rates of a current population observed for a specific calendar year, the life table death rate is equivalent to the observed death rates of the current population:

m_x_ = (d_x_)/(L_x_) = M_x_ = (D_x_)/(P_x_) The age-specific life table death rate equals the life table number of age-specific deaths divided by the life table age-specific person-years lived, which equals the observed age-specific death rate, which equals the observed age-specific number of deaths divided by the observed age-specific midyear population.

where D_x_ is the Beers’ smoothed number of deaths adjusted for not-stated age and Hispanic-origin and race misclassification on the death certificate (for the Hispanic and American Indian and Alaska Native, Asian, Black, and White non-Hispanic race groups), and P_x_ is the Beers’ smoothed population at risk of dying between ages x and x + 1. Then,

q_x_ = (M_x_)/(1 + (1)/(2) M_x_) = (D_x_)/(P_x_ + (1)/(2) D_x_) The age-specific probability of death equals the observed age-specific death rate divided by one plus one-half multiplied by the age-specific death rate, which equals the age-specific number of deaths divided by the midyear age-specific population count plus one-half the age-specific number of deaths. [5]

This procedure is used to estimate vital statistics age-specific probabilities of death for ages 1–99.

#### Calculation of q_x_ at age 0

The higher mortality observed in infancy is associated with a high concentration of deaths occurring at the beginning of the age interval rather than in the middle. As a result, it is best to assign deaths to the appropriate birth cohorts whenever possible. Consequently, the probability of death at birth, q_0_, is calculated using a birth cohort method that uses a separation factor (f) defined as the proportion of infant deaths in year t occurring to infants born in the previous year (t – 1). The value f is estimated by categorizing infant deaths by date of birth. The probability of death is then calculated as:

q_0_ = (D_0_ (1 − f))/(B^t^) + (D_0_ (f))/(B^t − 1^) The probability of death in the first year of life equals the number of deaths at ages zero to one multiplied by one minus the separation factor divided by the number of births in the current year, plus the number of deaths at ages zero to one multiplied by the separation factor divided by the number of births in the previous year. [6]

where D_0_ is the number of infant deaths adjusted for not-stated age in 2023, B^t^ is the number of live births in 2023, and B^t-1^ is the number of live births in 2022. Table III shows separation factors and numbers of births for 2022 and 2023.

Table III

Births in 2022 and 2023, deaths in 2023 of infants born in 2022 and 2023, and separation factors, by Hispanic origin and race and sex: United States

Births, deaths, and separation factors | Total | | | Hispanic | | | Non-Hispanic
Births, deaths, and separation factors | Total | | | Hispanic | | | American Indian and Alaska Native | | | Asian | | | Black | | | White
Births, deaths, and separation factors | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
Births
2022 | 3,667,758 | 1,874,446 | 1,793,312 | 937,421 | 477,401 | 460,020 | 25,721 | 13,063 | 12,658 | 218,994 | 112,726 | 106,268 | 511,439 | 259,987 | 251,452 | 1,840,739 | 942,920 | 897,819
2023 | 3,596,017 | 1,839,794 | 1,756,223 | 945,200 | 482,254 | 462,946 | 24,571 | 12,505 | 12,066 | 215,738 | 111,542 | 104,196 | 491,494 | 249,931 | 241,563 | 1,787,051 | 916,170 | 870,881
Deaths in 2023
Infants born in 2022 | 2,659 | 1,455 | 1,202 | 565 | 299 | 266 | 41 | 26 | 15 | 73 | 37 | 37 | 779 | 416 | 365 | 1,049 | 601 | 448
Infants born in 2023 | 17,486 | 9,652 | 7,836 | 4,185 | 2,305 | 1,880 | 185 | 103 | 81 | 669 | 384 | 284 | 4,595 | 2,474 | 2,119 | 6,959 | 3,881 | 3,078
Separation factor, f | 0.132 | 0.131 | 0.133 | 0.119 | 0.115 | 0.124 | 0.180 | 0.204 | 0.152 | 0.099 | 0.088 | 0.114 | 0.145 | 0.144 | 0.147 | 0.131 | 0.134 | 0.127

NOTE: People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

### Probabilities of dying at the oldest ages for the total, Black non-Hispanic, and White non-Hispanic populations

Medicare data are used to supplement vital statistics data for the estimation of q_x_ at the oldest ages. These data are more accurate because proof of age is required for enrollment in the Medicare program. Medicare data are used here to estimate the probability of dying for ages 66 and older for the total, Black non-Hispanic, and White non-Hispanic populations.

The method described in this section consists of the following steps. First, vital statistics and Medicare death rates are blended in the age range 66–99. Second, a logistic model is used to smooth the blended death rates in the age range 85–99 and predict death rates for ages 100–120. Third, final resulting death rates, M_x_, are converted to q_x_.

For ages 66–94, vital statistics death rates, M_x_^V^, and Medicare death rates, M_x_^M^, are blended with a weighting process that gives gradually declining weight to vital statistics data and gradually increasing weight to Medicare data. For ages 95–99, M_x_^M^ is used exclusively. Blended M_x_ is obtained as follows:

M_x_ = (1)/(30) [(95 − x) M_x_^V^ + (x − 65) M_x_^M^] The age-specific death rate when ages are 66 through 94 equals the sum of the product of the age-specific death rate at age x based on vital statistics data and 95 minus age x and the product of the age-specific death rate at age x based on Medicare data and age x minus 65, divided by 30; and the age-specific death rate at ages 95 through 100 equals the age-specific death rate at ages 95 through 100 based on Medicare data. [7]

when x = 66,...,94

and M_x_ = M_x_^M^

when x = 95,...,99. M_x_^M^ is estimated as follows:

M_x_^M^ = (D_x_^M^)/(P_x_^M^) The Medicare age-specific death rate when ages are 66 through 99 equals the age-specific number of deaths in Medicare data for ages 66 through 99 divided by the age-specific population alive in the middle of the year in Medicare data for ages 66 through 99.

where D_x_^M^ is the age-specific Medicare death count, and P_x_^M^ is the age-specific Medicare midyear population count.

A logistic model proposed by Kannisto is then used to smooth M_x_ in the age range 85–99 and predict M_x_ in the age range 100–120 (25). The start of the modeled age range varies by race- and ethnicity-specific population because it is a function of the age at which the rate of change in the age-specific death rates peaks. Currently, the rate of change in the age-specific death rate rises steadily up to about ages 80–85 and then begins to decline. As a result, it is difficult to model a large age span, such as 65–100, with one simple model without over smoothing and consequently altering the underlying mortality pattern observed in the population of interest (26). Further, the observed data for the age range 65–85 or so is reliable and robust, as indicated by the very close similarity between vital statistics and Medicare death rates, so it is unnecessary to model (smooth) the entire age span (65–100).

The Kannisto model is a simple form of a logistic model in which the logit of u_x_ (or the natural log of the odds of u_x_) is a linear function of age, x (25). It is expressed as:

ln ((u_x_)/(1 − u_x_)) = ln (α) + β x The natural log of the odds of the force of mortality equals the natural log of alpha plus beta x. [8]

where u_x_, the force of mortality (or the instantaneous death rate), is defined as:

u_x_ = (α e^β x^)/(1 + α e^β x^) The force of mortality at age x equals alpha times the exponential of beta x divided by one plus alpha times the exponential of beta x.

Because u_x_ is not directly observed but is closely approximated by m_x_, and m_x_ = M_x_, then the logit of M_x_ is modeled instead. A maximum-likelihood generalized linear-model estimation procedure is used to fit the following model in the age range 85–99:

ln [(M_x_)/(1 − M_x_)] = ln (α) + β x The natural log of the odds of M x is equal to the natural log of alpha plus beta x.

Then, the estimated parameters are used to predict M̅_x_ as follows:

M¯_x_ = (e^a^ e^b x^)/(1 + e^a^ e^b x^)

or, equivalently,

M¯_x_ = (e^a + b x^)/(1 + e^a + b x^) The predicted age-specific death rate equals the exponential of estimated parameter a times the exponential of estimated parameter b times x divided by one plus the exponential of estimated parameter a times the exponential of estimated parameter b times x. Or, equivalently, the predicted age-specific death rate equals the exponential of estimated parameter a plus estimated parameter b times x divided by one plus the exponential of estimated parameter a plus estimated parameter b times x. [10]

where a and b are the predicted values of parameters ln(α) and β, respectively, given by fitting model [9]. Estimated parameters and the starting age for the modeled age span by population in 2023 are presented in Table IV.

Table IV

Estimated parameters α and β used for predicting m_x_ and starting age of modeled age span: U.S. Life Tables, 2023

Parameter | Total | | | Black, non-Hispanic | | | White, non-Hispanic
Parameter | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
Starting age | 85 | 86 | 85 | 86 | 86 | 86 | 85 | 86 | 85
ln(α) (standard error) | -13.8063 (0.071) | -13.84779 (0.297) | -14.36963 (0.030) | -11.57264 (0.237) | -11.63354 (0.498) | -12.14837 (0.229) | -14.08533 (0.066) | -14.35036 (0.265) | -14.61157 (0.041)
β (standard error) | 0.1341625 (0.001) | 0.1365423 (0.003) | 0.1392481 (0.000) | 0.1081698 (0.003) | 0.1109480 (0.006) | 0.1135587 (0.003) | 0.1377844 (0.001) | 0.1426468 (0.003) | 0.1424322 (0.000)

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Finally, the predicted probability of death, q̅_x_, for ages 85–120 is estimated by converting M̅_x_ as:

q¯_x_ = (M¯_x_)/(1 + (1)/(2) M¯_x_) The predicted probability of death equals the predicted age-specific death rate divided by one plus one-half the predicted age-specific death rate. [11]

The probability of death is extrapolated to age 120 to estimate the life table population until no survivors remain. This information is then used to estimate L_x_ for ages 100–120, which is used to close the table with the age category 100 and older, combined (discussed in the following section).

### Probabilities of dying at the oldest ages for the Hispanic, American Indian and Alaska Native non-Hispanic, and Asian non-Hispanic populations

As previously noted, Medicare data are unreliable for the Hispanic (regardless of race) and American Indian and Alaska Native and Asian (regardless of Hispanic origin) populations due to inconsistencies in the Medicare race and ethnicity classification system. As a result, other methods had to be used to estimate mortality at the oldest ages for these populations. Beyond age 80, mortality estimates based strictly on vital statistics for these three populations are too low, despite correction for ethnicity and race misclassification on the death certificate.

A consistent finding across diverse studies has been that Hispanic mortality in the adult and advanced ages varies between approximately 80% and 89% relative to that of the White non-Hispanic population (17,27,28). The Brass relational logit model takes advantage of the relationship between Hispanic and White non-Hispanic mortality previously identified and has been widely and successfully used to predict the mortality of one population relative to another at the older ages (29,30). Using the age-specific mortality pattern of the White non-Hispanic population as the standard, the Brass relational logit model is used to predict Hispanic mortality in the older ages. The standard is fit to Hispanic data in the age interval 45–80, and the predicted parameters are used to estimate the probabilities of death for ages 76–100. This method allows the relationship between the two populations in the younger ages to be extended to the older ages (17,29,30).

Although similar information is not available for the American Indian and Alaska Native non-Hispanic and Asian non-Hispanic populations, with a slight modification, the Brass relational logit model was successfully used to produce reliable complete period life tables for the American Indian and Alaska Native non-Hispanic population in Indian Health Service Contract Health Service Delivery Area counties (31). The choice of the White non-Hispanic population as the standard population is based on several factors. First, it is the most widely used comparison population in the study of racial and ethnic disparities given its social and economic privilege. Second, it is the largest population in the United States and has the most reliable mortality data. Third, the relationship between the age-specific mortality patterns of the American Indian and Alaska Native non-Hispanic and Asian non-Hispanic populations and the White non-Hispanic population remains constant throughout the age span 45–80 (45–84 for the non-Hispanic AIAN population). The assumption that this pattern continues to the oldest ages is reasonable because the final results are consistent with expected age-specific mortality patterns at the oldest ages (Figures I and II).

Figure I Age pattern of mortality for the Asian, non-Hispanic population: United States, 2023

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure I is a line graph showing the natural logarithm of the probability of dying by age based on vital statistics data and modeled data for the Asian, non-Hispanic population in 2023.

Figure II Age pattern of mortality for the American Indian and Alaska Native, non-Hispanic population: United States, 2023

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure II is a line graph of the natural logarithm of probability of dying by age, using vital statistics and modeled data for the American Indian and Alaska Native non-Hispanic population in 2023.

The Brass relational logit model expresses the age-specific mortality pattern of a population of interest as a function of the age-specific mortality pattern of a standard population and is expressed as:

Y¯_x_ = α + β Y_x_^S^ The predicted logit of the probability of death in the population of interest equals alpha plus beta multiplied by the logit of the probability of death in the standard population. [12]

where Y̅_x_ is the predicted logit of the probability of death, q_x_, in the population of interest, that is,

l o g i t [q_x_] = ln [(q_x_)/(1 − q_x_)] The logit of the probability of death at age x equals the natural log of the odds of the probability of death at age x.

Y_x_^S^ is the logit of the probability of death in the standard population, q_x_^S^, that is,

l o g i t [q_x_^S^] = ln [(q_x_^S^)/(1 − q_x_^S^)] The logit of the probability of death at age x of the standard population at age x equals the natural log of the odds of the probability of death at age x of the standard population.

α is the predicted parameter that measures the level of mortality of the population of interest relative to the standard population, and β is the predicted parameter that measures the slope of the mortality function of the population of interest relative to the standard population (3,14,30). Table V shows values of predicted α and β and their standard errors.

Table V

Estimated Brass relational logit model parameters α and β for the Hispanic, American Indian and Alaska Native non-Hispanic populations: U.S. Life Tables, 2023

Parameter | Hispanic | | | Non-Hispanic
Parameter | Hispanic | | | American Indian and Alaska Native | | | Asian
Parameter | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
α (standard error) | -0.3205457 (0.021) | -0.3521423 (0.027) | -0.1733808 (0.021) | -1.0903770 (0.057) | -1.2860400 (0.034) | -0.8601727 (0.071) | -0.1028543 (0.027) | -0.1914050 (0.025) | -0.0106462 (0.038)
β (standard error) | 0.9949207 (0.005) | 0.9771507 (0.006) | 1.0403240 (0.005) | 0.6200744 (0.013) | 0.5547067 (0.008) | 0.6883710 (0.016) | 1.1536070 (0.007) | 1.1222820 (0.006) | 1.1798890 (0.010)

NOTE: Hispanic people may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

A maximum-likelihood generalized linear-model estimation procedure was used to fit equation [12] in the age range 45–80 (45–84 for the American Indian and Alaska Native non-Hispanic population). The resulting predicted parameters α and β were then used to estimate the predicted probability of death for ages 76–120 (80–120 for the American Indian and Alaska Native non-Hispanic population). The value q_x_ was predicted to age 120 to estimate the life table population until no survivors remain, as was done for the other population groups. This information was then used to estimate L_x_ for ages 100–120, which was used to close the table with the age category 100 and older, combined (discussed in the next section).

Predicted q̅_x_ is estimated by transforming its logit, Y̅_x_, back as follows:

q¯_x_ = (exp [Y¯_x_])/(1 + exp [Y¯_x_]) = (exp [α + β Y_x_^S^])/(1 + exp [α + β Y_x_^S^]) The predicted probability of death equals the exponential function of the logit of the probability of death in the standard population divided by one plus the exponential function of the logit of the probability of death of the standard population. [13]

To ensure a smooth transition from vital q_x_^V^ and predicted q̅_x_, the two were blended from ages 76 to 80 (80 to 84 for the American Indian and Alaska Native non-Hispanic population) with a graduating process as follows:

q_x_ = (1)/(6) [(81 − x) q_x_^V^ + (x − 75) q¯_x_] For the Hispanic and Asian non-Hispanic populations, the probability of death when ages are 76 through 80 equals the sum of the product of the probability of death at age x based on vital statistics data and 81 minus age x and the product of the predicted probability of death at age x minus 75, divided by 6. For the American Indian and Alaska Native non-Hispanic population, the probability of death when ages are 80 through 84 equals the sum of the product of the probability of death at age x based on vital statistics data and 85 minus age x and the product of the predicted probability of at age x minus 79, divided by 6. [14]

when x = 76,...,80,

q_x_ = (1)/(6) [(85 − x) q_x_^V^ + (x − 79) q¯_x_] For the Hispanic and Asian non-Hispanic populations, the probability of death when ages are 76 through 80 equals the sum of the product of the probability of death at age x based on vital statistics data and 81 minus age x and the product of the predicted probability of death at age x minus 75, divided by 6. For the American Indian and Alaska Native non-Hispanic population, the probability of death when ages are 80 through 84 equals the sum of the product of the probability of death at age x based on vital statistics data and 85 minus age x and the product of the predicted probability of at age x minus 79, divided by 6.

when x = 80,...,84.

Finally, to close the table at age 100 and older (combined), _∞_q_100_ is set equal to 1.0 because all survivors to this age will die at some point in the open-ended age interval. Once q_x_ is obtained for each single year of age, the other life table functions are easily calculated.

### Calculation of remaining life table functions for all groups

#### Survivor function (l_x_)

The life table radix, l_0_, is set at 100,000. For ages greater than 0, the number of survivors remaining at exact age x is calculated as:

l_x =_ l_x − 1_ (1 − q_x − 1_) The number of survivors at age x equals the number of survivors at age x minus one multiplied by one minus the probability of death at age x minus one. [15]

#### Decrement function (d_x_)

The number of deaths occurring between ages x and x + 1 is calculated from the survivor function:

d_x_ = l_x_ − l_x + 1_ = l_x_ q_x_ The number of deaths at age x equals the number of survivors at age x minus the number of survivors at age x plus one. This in turn equals the number of survivors at age x multiplied by the probability of death at age x. [16]

Note that

_∞_d_100_ = _∞_l_100_ because _∞_q_100_ = 1.0.

#### Person-years lived (L^x^)

Person-years lived for ages 1–99 is calculated assuming that the survivor function declines linearly between ages x and x + 1. This gives the formula:

L_x_ = (1)/(2) (l_x_ + l_x + 1_) = l_x_ − (1)/(2) d_x_ The number of person-years lived at age x equals the number of survivors at age x plus the number of survivors at age x plus one, divided by 2. This in turn equals the number of survivors at age x minus one-half the number of deaths at age x. [17]

For x = 0, the separation factor f is used to calculate L_0_:

L_0_ = f l_0_ + (1 − f) l_1_ The number of person-years lived at age zero equals the separation factor multiplied by the number of survivors at age zero plus the product of one minus the separation factor and the number of survivors at age one. [18]

Finally, _∞_L_100_ is estimated as the sum of the extrapolated L_x_ values for ages 100–120.

#### Person-years lived at and above age x (T^x^)

T_x_ is calculated by summing L_x_ values at and above age x:

T_x_ = ∑_x = 0_^∞^ L_x_ The total number of person-years lived at age x equals the sum of the number of person-years lived at age x and older. [19]

#### Life expectancy at age x (e_x_)

Life expectancy at exact age x is calculated as:

e_x_ = (T_x_)/(l_x_) Life expectancy at age x equals the total number of person-years lived at age x divided by the number of survivors at age x. [20]

### Causes of death contributing to changes in life expectancy

To measure changes in mortality, a discrete method, developed by Arriaga (12,32,33), was used to estimate the contribution of mortality change by causes of death based on changes in life expectancy, which is described as a procedure that “estimates the number of years added to or removed from life expectation because of the decrease or increase (respectively) of the central mortality rates of life tables” (32). With this method one can partition the change in life expectancy over time or between two separate groups of populations. In this report, Arriaga’s technique is used to partition by cause of death changes in life expectancy at birth in the United States from 2022 to 2023.

The method partitions changes into component additive parts and identifies the causes of death having the greatest influence, positive or negative, on changes in life expectancy based on rankable causes of death (12,32,33). This method is used by NCHS annually to analyze changes in life expectancy (13).

### Abridging the complete life table

An abridged or collapsed version of the complete life table can be calculated in which life table functions are shown for 5-year rather than single-year age intervals. It is often desirable to summarize the life table and save space when publishing life table data by single years of age. The abridgement of the complete life table is simplified by an important property of three of the six life table functions. The l_x_, T_x_, and e_x_ functions describe exact age x, that is, the beginning of the age interval x to x + n (where n denotes the length of the age interval; for 5-year age intervals, n = 5). Life expectancy at age 20 (e_20_), for example, has the same value regardless of whether the age interval is 20–21 or 20–25. Consequently, the values l_x_, T_x_, and e_x_ can be extracted at 5-year intervals from the complete life table and placed into the abridged life table (compare l_x_, T_x_, and e_x_ in Table VI with the same functions in Table 1). It is also illustrative to compare values for e_x_ and l_x_ in Tables A and B with their corresponding values presented in Tables 1–18.

Table VI

Life table for the total population: United States, 2023

Age (years) | Probability of dying between ages x and x + n | Number surviving toage x | Number dying between ages x and x + n | Person-years lived between ages x and x + n | Total number of person-years lived above age x | Expectation of life at age x
Age (years) | _n _ q _x_ | l _x_ | _n _ d _x_ | _n _ L _x_ | T _x_ | e _x_
0–1 | 0.005588 | 100,000 | 559 | 99,515 | 7,842,141 | 78.4
1–5 | 0.001095 | 99,441 | 109 | 397,502 | 7,742,626 | 77.9
5–10 | 0.000622 | 99,332 | 62 | 496,495 | 7,345,124 | 73.9
10–15 | 0.000835 | 99,271 | 83 | 496,197 | 6,848,629 | 69.0
15–20 | 0.002886 | 99,188 | 286 | 495,306 | 6,352,432 | 64.0
20–25 | 0.004789 | 98,901 | 474 | 493,388 | 5,857,126 | 59.2
25–30 | 0.006280 | 98,428 | 618 | 490,665 | 5,363,739 | 54.5
30–35 | 0.008395 | 97,810 | 821 | 487,069 | 4,873,074 | 49.8
35–40 | 0.010391 | 96,989 | 1,008 | 482,514 | 4,386,005 | 45.2
40–45 | 0.013260 | 95,981 | 1,273 | 476,826 | 3,903,491 | 40.7
45–50 | 0.016842 | 94,708 | 1,595 | 469,739 | 3,426,666 | 36.2
50–55 | 0.023756 | 93,113 | 2,212 | 460,346 | 2,956,927 | 31.8
55–60 | 0.035388 | 90,901 | 3,217 | 446,970 | 2,496,581 | 27.5
60–65 | 0.052261 | 87,684 | 4,582 | 427,512 | 2,049,611 | 23.4
65–70 | 0.073440 | 83,102 | 6,103 | 400,927 | 1,622,099 | 19.5
70–75 | 0.104441 | 76,999 | 8,042 | 365,878 | 1,221,172 | 15.9
75–80 | 0.161626 | 68,957 | 11,145 | 318,440 | 855,294 | 12.4
80–85 | 0.261404 | 57,812 | 15,112 | 252,816 | 536,853 | 9.3
85–90 | 0.415132 | 42,699 | 17,726 | 169,653 | 284,038 | 6.7
90–95 | 0.613791 | 24,974 | 15,329 | 84,145 | 114,385 | 4.6
95–100 | 0.793818 | 9,645 | 7,656 | 25,847 | 30,240 | 3.1
100 and older | 1.000000 | 1,989 | 1,989 | 4,393 | 4,393 | 2.2

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

The q_x_, d_x_, and L_x_ functions, in contrast, describe the age interval x to x + n. In fact, for abridged life tables, the notation for these functions is different (_n_q_x_, _n_d_x_, and _n_L_x_, respectively). As a result, _5_q_20_ is the probability of dying between ages 20 and 25 and will be somewhat larger than q_20_, the probability of dying between ages 20 and 21. Considering this, _n_q_x_, _n_d_x_, and _n_L_x_ must be recalculated in the abridged life table. It is simplest to begin with _n_d_x_. The calculations are made for all but the final age interval as:

_n_d x = l_x_ − l_x + n_ The number of deaths at age x to x plus n equals the number of survivors at age x minus the number of survivors at age x plus n.

_n_q x = (_n_d x)/(l_x_) The probability of dying at ages x to x plus n equals the number of deaths at ages x to x plus n divided by the number of survivors at age x.

_n_L x = T_x_ − T_x + n_ The number of person-years lived at ages x to x plus n equals the total number of years lived at age x minus the total number of years lived at age x plus n.

Note that for the open-ended interval, ages 100 and older, _∞_d_100_ = _∞_l_100_ because _∞_q_100_ = 1.0, and _∞_L_100_ = T_100_. Table VI shows each of the life table functions for the 2023 U.S. total population abridged from Table 1.

## Acknowledgments

The authors are grateful for the reviews and comments provided by Robert N. Anderson, Statistical Analysis and Surveillance Branch (SASB), Division of Vital Statistics (DVS); Andrés A. Berruti, DVS; and Amy M. Branum, Office of the Director. The authors thank Sally C. Curtin, SASB, for content review and Brady Hamilton, Danielle Ely, and Anne Driscoll, SASB, for their assistance with birth data. The National Center for Health Statistics Office of Information Services, Information Design and Publishing Staff edited and produced this report: editor Jane Sudol and typesetter and graphic designer Jiale Feng.

## References

1 Shryock HS, Siegel JS, Larmon EA. The methods and materials of demography, vol 2. U.S. Census Bureau. 1971.
2 Moriyama IM, Gustavus SO. Cohort mortality and survivorship: United States death-registration states, 1900–1968. National Center for Health Statistics. Vital Health Stat 3. 1972 Nov;(16):1–36. Available from: https://www.cdc.gov/nchs/data/series/sr_03/sr03_016.pdf.
3 Preston SM, Heuveline P, Guillot M. Demography: Measuring and modeling population processes. Oxford, England: Blackwell Publishers. 2001.
4 Sirken MG. Comparison of two methods of constructing abridged life tables by reference to a “standard” table. Vital Health Stat 2. 1966 Mar;(4):1–19. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_004.pdf.
5 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist. 1997;62(210):58782–90. Available from: https://www.govinfo.gov/content/pkg/FR-1997-10-30/pdf/97-28653.pdf.
6 Office of Management and Budget. Race and ethnic standards for federal statistics and administrative reporting. Statistical Policy Directive 15. 1977. Available from: https://wonder.cdc.gov/wonder/help/populations/bridged-race/directive15.html.
7 Heron M. Comparability of race-specific mortality data based on 1977 versus 1997 reporting standards. Natl Vital Stat Rep. 2021 Apr;70(3):1–31. PMID: 34029180. DOI: 10.15620/cdc:103476.
8 Arias E, Heron M, Hakes JK. The validity of race and Hispanic-origin reporting on death certificates in the United States: An update. Vital Health Stat 2. 2016 Aug; (172):1–21. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_172.pdf.
9 Arias E, Schauman WS, Eschbach K, Sorlie PD, Backlund E. The validity of race and Hispanic origin reporting on death certificates in the United States. National Center for Health Statistics. Vital Health Stat 2. 2008 Oct;(148):1–32. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_148.pdf.
10 Arias E, Xu JQ, Curtin S, Bastian B, Tejada-Vera B. Mortality profile of the non-Hispanic American Indian or Alaska Native population, 2019. Natl Vital Stat Rep. 2021 Nov;70(12):1–27. PMID: 34842523. DOI: 10.15620/cdc:110370.
11 Waldron I. Recent trends in sex mortality ratios for adults in developed countries. Soc Sci Med. 1993;36(4):451–62.8434270
12 Kochanek KD, Maurer JD, Rosenberg HM. Causes of death contributing to changes in life expectancy: United States, 1984–89. National Center for Health Statistics. Vital Health Stat 20. 1994;(23):1–40. Available from: https://www.cdc.gov/nchs/data/series/sr_20/sr20_023.pdf.
13 Kochanek KD, Murphy SL, Jiaquan Xu, Arias E. Deaths: Final data for 2023. Natl Vital Stat Rep. [Forthcoming].
14 Arias E. United States life tables, 2008. Ntl Vital Stat Rep. 2012 Sep;61(3):1–64. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr61/nvsr61_03.pdf.
15 Arias E, Bastian B, Xu JQ, Tejada-Vera B. U.S. State Life Tables, 2018. Natl Vital Stat Rep. 2021 Mar;70(1):1–18. PMID: 33814036. DOI: 10.15620/cdc:101128.
16 Arias E, Rostron BL, Tejada-Vera B. United States life tables, 2005. Natl Vital Stat Rep. 2010 Mar;58(10):1–132. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr58/nvsr58_10.pdf.
17 Arias E. United States life tables by Hispanic origin. National Center for Health Statistics. Vital Health Stat 2. 2010 Oct;(152):1–41. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_152.pdf.
18 Arias E, Xu JQ. United States Life Tables, 2018. Natl Vital Stat Rep. 2020 Nov;69(12):1–45. PMID: 33270553. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr69/nvsr69-12-508.pdf.
19 Ingram DD, Parker JD, Schenker N, Weed JA, Hamilton B, Arias E, Madans JH. United States Census 2000 population with bridged race categories. Vital Health Stat 2. 2003 Sep;(135):1–62. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_135.pdf.
20 Bell FC, Miller ML. Life tables for the United States Social Security area 1900–2100. Baltimore, MD: Social Security Administration. SSA Pub. No. 11–11536. 2005.
21 Research Data Assistance Center. Introduction to the use of Medicare data for research. Minneapolis, MN: University of Minnesota School of Public Health. 2004.
22 Ely DM, Driscoll AK. Infant mortality in the United States, 2023: Data from the period linked birth/infant death file. Natl Vital Stat Rep. 2025 Jun;74(7):1–20. DOI: 10.15620/cdc/174592.40570233
23 Ely DM, Driscoll AK. Infant mortality in the United States, 2022: Data From the period linked birth/infant death file. Natl Vital Stat Rep. 2024 Jul; 73(5):1–19. DOI: 10.15620/cdc/157006.
24 Arias E, Miniño A, Curtin SC, Tejada-Vera B. U.S. decennial life tables for 2009–2011, United States life tables. Natl Vital Stat Rep. 2020 Aug;69(8):1–12. PMID: 33054922. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr69/NVSR69-08-508.pdf.
25 Thatcher AR, Kannisto V, Vaupel JW. The force of mortality at ages 80 to 120. Odense, Denmark: Odense University Press. 1998.
26 Andreev KF, Bourbeau RR. Frailty modeling of Canadian and Swedish mortality at adult and advanced ages. Population Association of America Annual Meeting. 2007.
27 Elo IT, Turra CM, Kestenbaum B, Fergusson BR. Mortality among elderly Hispanics in the United States: Past evidence and new results. Demography. 2004 Feb; 41(1):109–28.15074127
28 Turra CM, Elo IT. The impact of salmon bias on the Hispanic mortality advantage: New evidence from Social Security data. Popul Res Policy Rev. 2008;27(5):515–30.19122882
29 Brass W. On the scale of mortality. In: Brass W, editor. Biological aspects of demography. London: Taylor and Francis. 99–110. 1971.
30 Himes CL, Preston SH, Condran GA. A relational model of mortality at older ages in low mortality countries. Popul Stud 1994;48(2):269–91.
31 Arias E, Xu JQ, Jim MA. Period life tables for the non-Hispanic American Indian and Alaska Native population, 2007– 2009. Am J Public Health. 2014 Jun;104 Suppl 3(Suppl 3):S312–9. DOI: 10.2105/AJPH.2013.301635.
32 Arriaga EE. Changing trends in mortality decline during the last decades. Part 3: In: Ruzicka L, Wunsch G, Kane P, editors. Differential mortality: Methodological issues and biosocial factors. Oxford, England: Clarendon Press. 1989.
33 Arriaga EE. Measuring and explaining the change in life expectancies. Demography 1984;21(1):83–96.6714492

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/.

For questions or general information about NCHS: Tel: 1–800–CDC–INFO (1–800–232–4636) • TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs • Online request form: https://www.cdc.gov/info