# Volume 74, Number 4 Deaths: Final Data for 2022

### Objectives

This report presents final 2022 data on U.S. deaths, death rates, life expectancy, infant and maternal mortality, and trends by selected characteristics such as age, sex, Hispanic origin and race, state of residence, and cause of death.

### Methods

Information reported on death certificates is presented in descriptive tabulations. The original records are filed in state registration offices. Statistical information is compiled in a national database through the Vital Statistics Cooperative Program of the National Center for Health Statistics. Causes of death are processed according to the International Classification of Diseases, 10th Revision. Beginning in 2018, all states and the District of Columbia were using the 2003 revised certificate of death for the entire year, which includes the 1997 Office of Management and Budget revised standards for race. Data based on these revised standards are not completely comparable to previous years.

### Results

In 2022, a total of 3,279,857 deaths were reported in the United States. The age-adjusted death rate was 798.8 deaths per 100,000 U.S. standard population, a decrease of 9.2% from the 2021 rate. Life expectancy at birth was 77.5 years, an increase of 1.1 years from 2021. Age-specific death rates decreased from 2021 to 2022 for age groups 15–24, 25–34, 35–44, 45–54, 55–64, 65–74, 75–84, and 85 and older and increased for age groups 1–4 and 5–14. In 2022, the 10 leading causes of death remained the same as in 2021, although four causes changed rank. Heart disease remained the top leading cause, followed by cancer. The infant mortality rate, 5.60 deaths per 1,000 live births in 2022, increased 2.9% from the rate in 2021 (5.44).

### Conclusions

In 2022, the age-adjusted death rate decreased and life expectancy at birth increased for the total, male, and female populations, primarily due to the decrease in deaths from COVID-19.

## Highlights

### Mortality experience in 2022

- In 2022, a total of 3,279,857 resident deaths were registered in the United States, a decrease of 184,374 deaths compared with 2021 (3,464,231). The 1-year decrease in the number of deaths was primarily driven by the decrease in deaths from COVID-19.
- The crude death rate was 984.1 deaths per 100,000 population. The age-adjusted death rate, which accounts for the aging of the population, was 798.8 deaths per 100,000 U.S. standard population.
- The age-adjusted death rate for the American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native) population (947.9) was 1.2 times greater than for the White non-Hispanic (subsequently, White) population (822.2).
- The age-adjusted death rate for the Black non-Hispanic (subsequently, Black) population (1,002.8) was 1.2 times greater than for the White population (822.2).
- The age-adjusted death rate for the White population (822.2) was 2.0 times greater than for the Asian non-Hispanic (subsequently, Asian) population (417.5) and 1.3 times greater than for the Hispanic population (614.7).
- The ratio of the age-adjusted rate for the White population (822.2) to that of the Native Hawaiian or Other Pacific Islander non-Hispanic (subsequently, Native Hawaiian or Other Pacific Islander) population (782.0) was 1.1.
- Life expectancy at birth was 77.5 years for the total population, 74.8 for males, and 80.2 for females.
- The 15 leading causes of death in 2022 were:
  1. Diseases of heart (heart disease)
  2. Malignant neoplasms (cancer)
  3. Accidents (unintentional injuries)
  4. COVID-19
  5. Cerebrovascular diseases (stroke)
  6. Chronic lower respiratory diseases
  7. Alzheimer disease
  8. Diabetes mellitus (diabetes)
  9. Nephritis, nephrotic syndrome and nephrosis (kidney disease)
  10. Chronic liver disease and cirrhosis
  11. Intentional self-harm (suicide)
  12. Influenza and pneumonia
  13. Essential hypertension and hypertensive renal disease (hypertension)
  14. Septicemia
  15. Parkinson disease
- In 2022, the infant mortality rate (IMR) was 5.60 infant deaths per 1,000 live births.
- The 10 leading causes of infant death were:
  1. Congenital malformations, deformations and chromosomal abnormalities (congenital malformations)
  2. Disorders related to short gestation and low birth weight, not elsewhere classified (low birth weight)
  3. Sudden infant death syndrome (SIDS)
  4. Accidents (unintentional injuries)
  5. Newborn affected by maternal complications of pregnancy (maternal complications)
  6. Newborn affected by complications of placenta, cord and membranes (cord and placental complications)
  7. Bacterial sepsis of newborn
  8. Respiratory distress of newborn
  9. Intrauterine hypoxia and birth asphyxia
  10. Diseases of the circulatory system

### Comparison with previous year

- The age-adjusted death rate decreased 9.2% from 879.7 per 100,000 standard population in 2021 to 798.8 in 2022.
- Life expectancy for the total population increased 1.1 years from 76.4 in 2021 to 77.5 in 2022.
- From 2021 to 2022, life expectancy at birth increased by 1.3 years for males (from 73.5 to 74.8) and by 0.9 year for females (79.3 to 80.2).
- Life expectancy for females (80.2) was 5.4 years higher than for males (74.8), a decrease of 0.4 year from 2021.
- The difference in life expectancy between the Black and White populations decreased 0.8 year from 5.5 years in 2021 to 4.7 years in 2022.
- From 2021 to 2022, life expectancy increased for Hispanic males (2.4 years), American Indian and Alaska Native males (2.3 years), American Indian and Alaska Native females (2.1 years), Hispanic females (1.7 years), Black males and females (1.5 years each), Asian males and White males (1.1 years each), Asian females (0.7 year), and White females (0.6 year).
- The 15 leading causes of death remained the same in 2022 as in 2021, although some causes changed ranks.
- Age-adjusted death rates decreased significantly in 2022 from 2021 for 11 of the 15 leading causes of death: heart disease, cancer, unintentional injuries, COVID-19, stroke, Chronic lower respiratory diseases, Alzheimer disease, diabetes, Chronic liver disease and cirrhosis, hypertension, and Parkinson disease. Significant increases occurred in 2022 from 2021 for 2 of the 15 leading causes of death: kidney disease and Influenza and pneumonia.
- The age-adjusted death rate decreased in 2022 from 2021 for alcohol-induced causes (6.3%).
- The age-adjusted rate for drug-induced causes did not change significantly in 2022 from 2021.
- The increase in life expectancy at birth for the total population in 2022 was mainly due to decreases in mortality from COVID-19, heart disease, cancer, unintentional injuries, and homicide.
- Among external causes of injury death, unintentional poisoning has been the leading mechanism of injury mortality since 2011.
- IMR increased 2.9% from 5.44 infant deaths per 1,000 live births in 2021 to 5.60 in 2022.
- The 10 leading causes of infant death remained the same in 2022 as in 2021, although two causes, Intrauterine hypoxia and birth asphyxia and Diseases of the circulatory system, changed ranks.

## Introduction

This report presents detailed 2022 data on deaths and death rates according to demographic and medical characteristics. These data provide information on mortality patterns among residents of the United States by such variables as age, sex, Hispanic origin and race, state of residence, and cause of death. Information on these mortality patterns is key to understanding changes in the health and well-being of the U.S. population (1). Companion reports present additional details on leading causes of death and life expectancy in the United States (2,3).

Cause-of-death statistics presented in this report are classified according to the International Classification of Diseases, 10th Revision (ICD–10) (4–6). Detail on cause-of-death classification is provided in Technical Notes of this report. The COVID-19 pandemic that began in 2020 continued to have a substantial impact on the mortality profile of the U.S. population for 2022.

Mortality data can be used to monitor and evaluate the health status of the United States in terms of current mortality levels and long-term mortality trends, and to identify segments of the U.S. population at greater risk of death from specific diseases and injuries. Differences in death rates among various demographic subpopulations, including racial and ethnic groups, may reflect subpopulation differences in factors such as socioeconomic status, access to medical care, and the prevalence of specific risk factors in a particular subpopulation.

The 2003 revision of the U.S. Standard Certificate of Death uses the revised 1997 Office of Management and Budget (OMB) standards for the collection of race and Hispanic ethnicity (7,8). The 1997 standards allow individuals to report more than one race and increase the race categories from four to five by separating the Asian and Pacific Islander groups. Beginning with the 2018 data year, all 50 states and the District of Columbia reported deaths based on the 2003 revision for the entire year, so the revised standards became the official standards for presenting mortality data by race and ethnicity (9). The Hispanic category did not change, remaining consistent with reports before 2018.

The race and ethnicity categories in this report follow the 1997 OMB revised race and Hispanic-origin standards. These categories differ from the bridged-race categories used before 2018 (10). The new categories include Hispanic, single-race American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native), single-race Asian non-Hispanic (subsequently, Asian), single-race Black or African American non-Hispanic (subsequently, Black), single-race Native Hawaiian or Other Pacific Islander non-Hispanic (subsequently, Native Hawaiian or Other Pacific Islander), and single-race White non-Hispanic (subsequently, White). Because single-race data are not available for the entire United States before 2018, data by race for 2018 through 2022 are not completely comparable with bridged-race data used in earlier years, so comparisons should be made with this consideration (11).

In addition to the tabulations included in this report, more detailed analysis is possible by using the annual mortality public-use file. The data file may be downloaded from: https://www.cdc.gov/nchs/data_access/Vitalstatsonline.htm (12). Data file documentation is available from: https://www.cdc.gov/nchs/data/dvs/2022-Mortality-Public-Use-File-Documentation.pdf. The public-use file does not include geographic detail, but a file with this information may be available upon request (13). Death data also may be accessed from the Centers for Disease Control and Prevention’s (CDC) WONDER, a web-based system that makes the agency’s information resources available to public health professionals and the general public (14).

## Methods

Data in this report are based on information from all resident death certificates filed in the 50 states and the District of Columbia.

This report provides detailed death data in Tables 1–25. Tables showing data by state also provide information for the Commonwealth of the Northern Mariana Islands (Northern Marianas), Guam, Puerto Rico, and U.S. Virgin Islands.

Table 1 Number of deaths, death rate, and age-adjusted death rate, by Hispanic origin and race and sex: United States, 1940, 1950, 1960, 1970, 1980, 1990, 2000, and 2010–2022

[Excludes deaths of nonresidents of the United States. Data for specified race or Hispanic-origin groups other than non-Hispanic White and non-Hispanic Black should be interpreted with caution because of inconsistencies in reporting these items on death certificates and surveys, although misclassification is very minor for the Hispanic and non-Hispanic Asian or Pacific Islander populations; see Technical Notes in this report]

Hispanic origin and race and year | Number | | | Crude death rate^1^ | | | Age-adjusted death rate^2^
Hispanic origin and race and year | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
Table 1. Number of deaths, death rate, and age-adjusted death rate, by Hispanic origin and race and sex: United States, 1940, 1950, 1960, 1970, 1980, 1990, 2000, and 2010–2022
[Excludes deaths of nonresidents of the United States. Data for specified race or Hispanic-origin groups other than non-Hispanic White and non-Hispanic Black should be interpreted with caution because of inconsistencies in reporting these items on death certificates and surveys, although misclassification is very minor for the Hispanic and non-Hispanic Asian or Pacific Islander populations; see Technical Notes in this report]
Hispanic origin and race and year | Number | | | Crude death rate^1^ | | | Age-adjusted death rate^2^
Hispanic origin and race and year | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All origins and races^3^
2022 | 3,279,857 | 1,719,250 | 1,560,607 | 984.1 | 1,040.2 | 928.9 | 798.8 | 954.5 | 666.1
2021 | 3,464,231 | 1,838,108 | 1,626,123 | 1,043.8 | 1,118.2 | 970.8 | 879.7 | 1,048.0 | 733.3
2020 | 3,383,729 | 1,769,884 | 1,613,845 | 1,027.0 | 1,090.8 | 965.1 | 835.4 | 998.3 | 695.1
2019 | 2,854,838 | 1,473,823 | 1,381,015 | 869.7 | 911.7 | 829.0 | 715.2 | 846.7 | 602.7
2018 | 2,839,205 | 1,458,469 | 1,380,736 | 867.8 | 905.2 | 831.6 | 723.6 | 855.5 | 611.3
2017 | 2,813,503 | 1,439,111 | 1,374,392 | 863.8 | 897.2 | 831.4 | 731.9 | 864.5 | 619.7
2016 | 2,744,248 | 1,400,232 | 1,344,016 | 849.3 | 880.2 | 819.3 | 728.8 | 861.0 | 617.5
2015 | 2,712,630 | 1,373,404 | 1,339,226 | 844.0 | 868.0 | 820.7 | 733.1 | 863.2 | 624.2
2014 | 2,626,418 | 1,328,241 | 1,298,177 | 823.7 | 846.4 | 801.7 | 724.6 | 855.1 | 616.7
2013 | 2,596,993 | 1,306,034 | 1,290,959 | 821.5 | 839.1 | 804.4 | 731.9 | 863.6 | 623.5
2012 | 2,543,279 | 1,273,722 | 1,269,557 | 810.2 | 824.5 | 796.4 | 732.8 | 865.1 | 624.7
2011 | 2,515,458 | 1,254,978 | 1,260,480 | 807.3 | 818.7 | 796.3 | 741.3 | 875.3 | 632.4
2010 | 2,468,435 | 1,232,432 | 1,236,003 | 799.5 | 812.0 | 787.4 | 747.0 | 887.1 | 634.9
2000 | 2,403,351 | 1,177,578 | 1,225,773 | 854.0 | 853.0 | 855.0 | 869.0 | 1,053.8 | 731.4
1990 | 2,148,463 | 1,113,417 | 1,035,046 | 863.8 | 918.4 | 812.0 | 938.7 | 1,202.8 | 750.9
1980 | 1,989,841 | 1,075,078 | 914,763 | 878.3 | 976.9 | 785.3 | 1,039.1 | 1,348.1 | 817.9
1970 | 1,921,031 | 1,078,478 | 842,553 | 945.3 | 1,090.3 | 807.8 | 1,222.6 | 1,542.1 | 971.4
1960 | 1,711,982 | 975,648 | 736,334 | 954.7 | 1,104.5 | 809.2 | 1,339.2 | 1,609.0 | 1,105.3
1950 | 1,452,454 | 827,749 | 624,705 | 963.8 | 1,106.1 | 823.5 | 1,446.0 | 1,674.2 | 1,236.0
1940 | 1,417,269 | 791,003 | 626,266 | 1,076.4 | 1,197.4 | 954.6 | 1,785.0 | 1,976.0 | 1,599.4
Hispanic^4^
2022 | 275,684 | 155,240 | 120,444 | 433.0 | 481.0 | 383.7 | 614.7 | 748.8 | 498.4
2021 | 315,664 | 181,195 | 134,469 | 503.9 | 571.3 | 434.7 | 724.7 | 884.9 | 582.7
2020 | 305,708 | 175,585 | 130,123 | 498.6 | 567.8 | 428.2 | 723.6 | 903.8 | 570.1
2019 | 212,397 | 117,683 | 94,714 | 350.7 | 384.9 | 315.7 | 523.8 | 633.2 | 430.7
2018 | 204,719 | 113,045 | 91,674 | 341.9 | 373.9 | 309.3 | 524.1 | 633.1 | 431.7
2017 | 197,249 | 108,579 | 88,670 | 334.6 | 364.6 | 304.0 | 524.7 | 631.8 | 434.2
2016 | 188,254 | 103,532 | 84,722 | 327.6 | 356.8 | 297.7 | 525.8 | 631.8 | 436.4
2015 | 179,457 | 98,170 | 81,287 | 317.1 | 343.2 | 290.4 | 525.3 | 628.9 | 438.3
2014 | 169,387 | 92,474 | 76,913 | 305.8 | 330.1 | 281.0 | 523.3 | 626.8 | 437.5
2013 | 163,241 | 88,880 | 74,361 | 301.9 | 323.7 | 279.4 | 535.4 | 639.8 | 448.6
2012 | 156,419 | 85,238 | 71,181 | 295.0 | 316.5 | 272.7 | 539.1 | 643.9 | 452.5
2011 | 149,635 | 81,887 | 67,748 | 287.5 | 309.7 | 264.6 | 540.7 | 647.3 | 452.8
2010 | 144,490 | 79,622 | 64,868 | 286.2 | 310.8 | 260.9 | 558.6 | 677.7 | 463.4
2000 | 107,254 | 60,172 | 47,082 | 303.8 | 331.3 | 274.6 | 665.7 | 818.1 | 546.0
Non-Hispanic, single race^5^
American Indian and Alaska Native:
2022 | 23,613 | 12,721 | 10,892 | 975.4 | 1,062.4 | 890.2 | 947.9 | 1,084.3 | 816.1
2021 | 26,972 | 14,724 | 12,248 | 1,100.0 | 1,216.9 | 986.2 | 1,109.2 | 1,282.7 | 946.6
2020 | 24,725 | 13,431 | 11,294 | 1,016.5 | 1,123.4 | 913.2 | 1,036.2 | 1,205.9 | 881.5
2019 | 18,057 | 9,732 | 8,325 | 741.6 | 812.1 | 673.3 | 782.5 | 901.9 | 673.3
2018 | 17,790 | 9,678 | 8,112 | 735.9 | 813.5 | 660.8 | 790.8 | 918.7 | 673.1
Asian:
2022 | 89,591 | 46,137 | 43,454 | 441.9 | 472.3 | 413.6 | 417.5 | 501.7 | 350.7
2021 | 92,432 | 48,386 | 44,046 | 469.5 | 511.7 | 430.5 | 461.7 | 554.9 | 386.3
2020 | 91,175 | 47,699 | 43,476 | 470.8 | 515.8 | 429.6 | 457.7 | 557.4 | 378.5
2019 | 70,532 | 35,914 | 34,618 | 373.1 | 398.7 | 349.8 | 372.8 | 442.4 | 317.2
2018 | 68,768 | 35,089 | 33,679 | 367.2 | 393.4 | 343.3 | 381.2 | 454.1 | 324.1
Black:
2022 | 411,934 | 219,538 | 192,396 | 979.2 | 1,085.4 | 880.8 | 1,002.8 | 1,257.5 | 809.0
2021 | 449,764 | 238,599 | 211,165 | 1,074.5 | 1,185.8 | 971.4 | 1,118.0 | 1,374.0 | 917.2
2020 | 449,213 | 237,703 | 211,510 | 1,084.3 | 1,200.0 | 978.4 | 1,119.0 | 1,399.0 | 905.2
2019 | 346,677 | 181,363 | 165,314 | 842.5 | 921.8 | 769.9 | 884.0 | 1,092.8 | 724.9
2018 | 341,408 | 177,958 | 163,450 | 834.7 | 909.8 | 765.9 | 892.6 | 1,102.8 | 733.7
Native Hawaiian or Other Pacific Islander:
2022 | 4,592 | 2,461 | 2,131 | 722.1 | 765.3 | 677.9 | 782.0 | 859.5 | 705.4
2021 | 5,223 | 2,906 | 2,317 | 834.0 | 917.5 | 748.6 | 924.3 | 1,042.8 | 806.0
2020 | 4,439 | 2,489 | 1,950 | 723.5 | 804.6 | 641.1 | 821.3 | 947.9 | 699.8
2019 | 3,491 | 1,938 | 1,553 | 585.8 | 646.5 | 524.4 | 679.0 | 769.0 | 589.5
2018 | 3,277 | 1,786 | 1,491 | 558.9 | 605.4 | 511.8 | 675.7 | 758.1 | 597.3
White:
2022 | 2,448,093 | 1,267,526 | 1,180,567 | 1,247.6 | 1,299.7 | 1,196.1 | 822.2 | 972.1 | 692.7
2021 | 2,548,809 | 1,337,385 | 1,211,424 | 1,294.9 | 1,368.8 | 1,222.1 | 893.9 | 1,055.6 | 751.4
2020 | 2,484,072 | 1,278,612 | 1,205,460 | 1,262.4 | 1,317.7 | 1,208.6 | 834.7 | 985.0 | 703.1
2019 | 2,183,844 | 1,115,767 | 1,068,077 | 1,106.8 | 1,146.6 | 1,068.1 | 739.9 | 868.8 | 627.4
2018 | 2,182,552 | 1,108,848 | 1,073,704 | 1,104.8 | 1,138.2 | 1,072.3 | 748.7 | 878.0 | 636.5

^1^Rates are on an annual basis per 100,000 population in specified group; see Technical Notes.

^2^Age-adjusted rates are per 100,000 U.S. standard population. For method of computation, see Technical Notes.

^3^Includes origins and races not shown separately; see Technical Notes.

^4^Includes people of Hispanic origin of any race. The Hispanic-origin category is consistent with 1997 Office of Management and Budget (OMB) standards; see Technical Notes.

^5^Only one race was reported on the death certificate. Hispanic-origin and race categories are consistent with 1997 OMB standards; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 2 Number of deaths and death rate by age, and age-adjusted death rate, by Hispanic origin and race and sex: United States, 2022

[Rates are on an annual basis per 100,000 population in specified group; age-adjusted rates are per 100,000 U.S. standard population; see Technical Notes in this report. Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards. Data for specified categories other than Black non-Hispanic, single race and White non-Hispanic, single race3 should be interpreted with caution because of inconsistencies between reporting these items on death certificates and on censuses and surveys; see Technical Notes]

Hispanic origin and race and sex | All ages | Age group | | | | | | | | | | | Age not stated | Age-adjusted rate^2^
Hispanic origin and race and sex | All ages | Younger than 1^1^ | 1–4 | 5–14 | 15–24 | 25–34 | 35–44 | 45–54 | 55–64 | 65–74 | 75–84 | 85 and older | Age not stated | Age-adjusted rate^2^
| Number
Total | 3,279,857 | 20,553 | 4,156 | 6,239 | 35,232 | 74,369 | 111,605 | 183,284 | 417,541 | 668,581 | 824,903 | 933,291 | 103 | …
Male | 1,719,250 | 11,371 | 2,353 | 3,587 | 25,637 | 52,511 | 73,486 | 114,847 | 254,278 | 384,985 | 427,507 | 368,601 | 87 | …
Female | 1,560,607 | 9,182 | 1,803 | 2,652 | 9,595 | 21,858 | 38,119 | 68,437 | 163,263 | 283,596 | 397,396 | 564,690 | 16 | …
Single race^3^ | 3,260,336 | 19,576 | 3,959 | 6,001 | 34,287 | 72,863 | 110,088 | 181,423 | 414,713 | 665,106 | 821,717 | 930,500 | 103 | …
Male | 1,708,400 | 10,857 | 2,245 | 3,452 | 24,988 | 51,467 | 72,538 | 113,703 | 252,590 | 383,065 | 425,888 | 367,520 | 87 | …
Female | 1,551,936 | 8,719 | 1,714 | 2,549 | 9,299 | 21,396 | 37,550 | 67,720 | 162,123 | 282,041 | 395,829 | 562,980 | 16 | …
Two or more races^4^ | 19,521 | 977 | 197 | 238 | 945 | 1,506 | 1,517 | 1,861 | 2,828 | 3,475 | 3,186 | 2,791 | – | …
Male | 10,850 | 514 | 108 | 135 | 649 | 1,044 | 948 | 1,144 | 1,688 | 1,920 | 1,619 | 1,081 | – | …
Female | 8,671 | 463 | 89 | 103 | 296 | 462 | 569 | 717 | 1,140 | 1,555 | 1,567 | 1,710 | – | …
Hispanic, total^5^ | 275,684 | 4,765 | 869 | 1,386 | 8,035 | 13,791 | 17,794 | 25,143 | 39,748 | 49,780 | 54,345 | 60,018 | 10 | …
Male | 155,240 | 2,612 | 466 | 787 | 6,040 | 10,542 | 12,875 | 16,955 | 25,576 | 28,932 | 27,163 | 23,283 | 9 | …
Female | 120,444 | 2,153 | 403 | 599 | 1,995 | 3,249 | 4,919 | 8,188 | 14,172 | 20,848 | 27,182 | 36,735 | 1 | …
Hispanic, single race^3^ | 273,099 | 4,552 | 827 | 1,356 | 7,892 | 13,568 | 17,563 | 24,896 | 39,386 | 49,394 | 53,974 | 59,681 | 10 | …
Male | 153,772 | 2,502 | 442 | 769 | 5,938 | 10,380 | 12,727 | 16,807 | 25,358 | 28,709 | 26,974 | 23,157 | 9 | …
Female | 119,327 | 2,050 | 385 | 587 | 1,954 | 3,188 | 4,836 | 8,089 | 14,028 | 20,685 | 27,000 | 36,524 | 1 | …
American Indian and Alaska Native | 1,705 | 41 | 11 | 8 | 90 | 143 | 158 | 180 | 290 | 330 | 246 | 208 | – | …
Male | 1,001 | 25 | 10 | 3 | 58 | 99 | 118 | 123 | 175 | 193 | 108 | 89 | – | …
Female | 704 | 16 | 1 | 5 | 32 | 44 | 40 | 57 | 115 | 137 | 138 | 119 | – | …
Asian | 886 | 39 | 12 | 12 | 43 | 54 | 53 | 72 | 109 | 156 | 182 | 154 | – | …
Male | 486 | 17 | 7 | 9 | 28 | 41 | 34 | 47 | 69 | 88 | 86 | 60 | – | …
Female | 400 | 22 | 5 | 3 | 15 | 13 | 19 | 25 | 40 | 68 | 96 | 94 | – | …
Black | 5,353 | 305 | 62 | 54 | 257 | 440 | 438 | 544 | 714 | 880 | 808 | 851 | – | …
Male | 3,137 | 165 | 28 | 34 | 192 | 332 | 322 | 364 | 436 | 515 | 422 | 327 | – | …
Female | 2,216 | 140 | 34 | 20 | 65 | 108 | 116 | 180 | 278 | 365 | 386 | 524 | – | …
Native Hawaiian or Other Pacific Islander | 315 | 10 | 6 | 4 | 22 | 30 | 23 | 33 | 55 | 54 | 42 | 36 | – | …
Male | 191 | 7 | 3 | 1 | 16 | 24 | 17 | 25 | 38 | 35 | 15 | 10 | – | …
Female | 124 | 3 | 3 | 3 | 6 | 6 | 6 | 8 | 17 | 19 | 27 | 26 | – | …
White | 264,840 | 4,157 | 736 | 1,278 | 7,480 | 12,901 | 16,891 | 24,067 | 38,218 | 47,974 | 52,696 | 58,432 | 10 | …
Male | 148,957 | 2,288 | 394 | 722 | 5,644 | 9,884 | 12,236 | 16,248 | 24,640 | 27,878 | 26,343 | 22,671 | 9 | …
Female | 115,883 | 1,869 | 342 | 556 | 1,836 | 3,017 | 4,655 | 7,819 | 13,578 | 20,096 | 26,353 | 35,761 | 1 | …
Hispanic, two or more races^4^ | 2,585 | 213 | 42 | 30 | 143 | 223 | 231 | 247 | 362 | 386 | 371 | 337 | – | …
Male | 1,468 | 110 | 24 | 18 | 102 | 162 | 148 | 148 | 218 | 223 | 189 | 126 | – | …
Female | 1,117 | 103 | 18 | 12 | 41 | 61 | 83 | 99 | 144 | 163 | 182 | 211 | – | …
Non-Hispanic, total | 2,994,727 | 15,560 | 3,275 | 4,849 | 27,152 | 60,421 | 93,436 | 157,417 | 375,693 | 615,996 | 768,717 | 872,167 | 44 | …
Male | 1,557,750 | 8,627 | 1,881 | 2,796 | 19,568 | 41,863 | 60,349 | 97,367 | 227,139 | 354,078 | 399,232 | 344,814 | 36 | …
Female | 1,436,977 | 6,933 | 1,394 | 2,053 | 7,584 | 18,558 | 33,087 | 60,050 | 148,554 | 261,918 | 369,485 | 527,353 | 8 | …
Non-Hispanic, single race^3^ | 2,977,823 | 14,798 | 3,121 | 4,641 | 26,350 | 59,140 | 92,154 | 155,807 | 373,233 | 612,917 | 765,903 | 869,715 | 44 | …
Male | 1,548,383 | 8,224 | 1,798 | 2,679 | 19,021 | 40,982 | 59,552 | 96,374 | 225,671 | 352,385 | 397,802 | 343,859 | 36 | …
Female | 1,429,440 | 6,574 | 1,323 | 1,962 | 7,329 | 18,158 | 32,602 | 59,433 | 147,562 | 260,532 | 368,101 | 525,856 | 8 | …
American Indian and Alaska Native | 23,613 | 210 | 64 | 110 | 664 | 1,729 | 2,302 | 2,781 | 4,298 | 4,712 | 4,053 | 2,690 | – | …
Male | 12,721 | 120 | 32 | 61 | 447 | 1,097 | 1,461 | 1,663 | 2,442 | 2,491 | 1,923 | 984 | – | …
Female | 10,892 | 90 | 32 | 49 | 217 | 632 | 841 | 1,118 | 1,856 | 2,221 | 2,130 | 1,706 | – | …
Asian | 89,591 | 624 | 120 | 193 | 823 | 1,580 | 2,595 | 4,942 | 8,971 | 16,293 | 22,628 | 30,822 | – | …
Male | 46,137 | 356 | 70 | 110 | 569 | 1,097 | 1,661 | 3,071 | 5,562 | 9,376 | 11,746 | 12,519 | – | …
Female | 43,454 | 268 | 50 | 83 | 254 | 483 | 934 | 1,871 | 3,409 | 6,917 | 10,882 | 18,303 | – | …
Black | 411,934 | 5,800 | 1,116 | 1,502 | 9,366 | 17,383 | 23,234 | 35,376 | 73,375 | 96,857 | 80,186 | 67,734 | 5 | …
Male | 219,538 | 3,230 | 634 | 874 | 7,180 | 12,282 | 14,840 | 21,498 | 43,345 | 54,062 | 38,510 | 23,078 | 5 | …
Female | 192,396 | 2,570 | 482 | 628 | 2,186 | 5,101 | 8,394 | 13,878 | 30,030 | 42,795 | 41,676 | 44,656 | – | …
Native Hawaiian or Other Pacific Islander | 4,592 | 89 | 26 | 26 | 92 | 207 | 347 | 559 | 889 | 1,057 | 841 | 459 | – | …
Male | 2,461 | 49 | 18 | 14 | 71 | 141 | 219 | 315 | 501 | 544 | 401 | 188 | – | …
Female | 2,131 | 40 | 8 | 12 | 21 | 66 | 128 | 244 | 388 | 513 | 440 | 271 | – | …
White | 2,448,093 | 8,075 | 1,795 | 2,810 | 15,405 | 38,241 | 63,676 | 112,149 | 285,700 | 493,998 | 658,195 | 768,010 | 39 | …
Male | 1,267,526 | 4,469 | 1,044 | 1,620 | 10,754 | 26,365 | 41,371 | 69,827 | 173,821 | 285,912 | 345,222 | 307,090 | 31 | …
Female | 1,180,567 | 3,606 | 751 | 1,190 | 4,651 | 11,876 | 22,305 | 42,322 | 111,879 | 208,086 | 312,973 | 460,920 | 8 | …
Non-Hispanic, two or more races^4^ | 16,904 | 762 | 154 | 208 | 802 | 1,281 | 1,282 | 1,610 | 2,460 | 3,079 | 2,814 | 2,452 | – | …
Male | 9,367 | 403 | 83 | 117 | 547 | 881 | 797 | 993 | 1,468 | 1,693 | 1,430 | 955 | – | …
Female | 7,537 | 359 | 71 | 91 | 255 | 400 | 485 | 617 | 992 | 1,386 | 1,384 | 1,497 | – | …
Not stated or not classifiable origin^6^ | 9,446 | 228 | 12 | 4 | 45 | 157 | 375 | 724 | 2,100 | 2,805 | 1,841 | 1,106 | 49 | …
Male | 6,260 | 132 | 6 | 4 | 29 | 106 | 262 | 525 | 1,563 | 1,975 | 1,112 | 504 | 42 | …
Female | 3,186 | 96 | 6 | – | 16 | 51 | 113 | 199 | 537 | 830 | 729 | 602 | 7 | …
| Rate^7^
Total^8^ | 984.1 | 558.0 | 28.0 | 15.3 | 79.5 | 163.4 | 255.4 | 453.3 | 992.1 | 1,978.7 | 4,708.2 | 14,389.6 | … | 798.8
Male | 1,040.2 | 603.9 | 31.0 | 17.1 | 113.0 | 226.4 | 332.2 | 566.3 | 1,230.1 | 2,419.7 | 5,527.0 | 16,139.6 | … | 954.5
Female | 928.9 | 510.0 | 24.8 | 13.3 | 44.3 | 98.0 | 176.7 | 339.6 | 762.4 | 1,586.3 | 4,061.0 | 13,438.5 | … | 666.1
Single race^3^ | 1,008.7 | 569.7 | 28.5 | 15.6 | 81.0 | 165.5 | 257.9 | 456.9 | 999.0 | 1,990.6 | 4,736.1 | 14,482.1 | … | 804.5
Male | 1,065.9 | 617.9 | 31.6 | 17.5 | 115.4 | 229.2 | 335.3 | 570.4 | 1,238.1 | 2,434.4 | 5,560.3 | 16,254.3 | … | 961.5
Female | 952.4 | 519.3 | 25.3 | 13.6 | 45.0 | 99.2 | 178.4 | 342.5 | 767.9 | 1,595.6 | 4,084.7 | 13,519.9 | … | 670.6
Two or more races^5^ | 193.8 | 395.5 | 20.2 | 9.7 | 46.8 | 102.3 | 150.1 | 257.7 | 495.5 | 922.6 | 1,868.5 | 4,597.1 | … | 346.7
Male | 216.5 | 408.4 | 21.7 | 10.8 | 63.3 | 141.8 | 194.7 | 331.5 | 623.7 | 1,096.1 | 2,147.8 | 4,750.2 | … | 409.6
Female | 171.4 | 382.1 | 18.7 | 8.6 | 29.8 | 62.8 | 108.6 | 190.2 | 379.9 | 771.8 | 1,647.2 | 4,505.3 | … | 291.4
Hispanic, total^5^ | 433.0 | 477.4 | 22.2 | 13.1 | 74.4 | 142.1 | 196.3 | 327.7 | 702.5 | 1,522.8 | 3,682.6 | 11,107.1 | … | 614.7
Male | 481.0 | 514.1 | 23.4 | 14.6 | 109.3 | 209.7 | 270.9 | 432.1 | 905.9 | 1,900.2 | 4,368.6 | 12,379.5 | … | 748.8
Female | 383.7 | 439.4 | 21.0 | 11.6 | 37.8 | 69.4 | 114.0 | 218.4 | 499.9 | 1,193.7 | 3,183.0 | 10,427.8 | … | 498.4
Hispanic, single race^3^ | 443.4 | 480.5 | 22.3 | 13.5 | 75.9 | 144.3 | 199.0 | 331.7 | 710.4 | 1,540.2 | 3,721.6 | 11,208.1 | … | 621.4
Male | 492.3 | 518.9 | 23.4 | 15.0 | 111.6 | 213.1 | 274.8 | 437.5 | 915.8 | 1,920.8 | 4,413.5 | 12,496.2 | … | 757.1
Female | 393.1 | 440.8 | 21.1 | 11.9 | 38.5 | 70.4 | 115.3 | 220.8 | 505.5 | 1,208.0 | 3,217.6 | 10,520.6 | … | 503.7
American Indian and Alaska Native | 86.9 | 97.4 | * | * | 28.3 | 49.5 | 57.2 | 79.9 | 179.5 | 390.0 | 791.9 | 2,210.4 | … | 143.9
Male | 98.1 | 116.8 | * | * | 35.6 | 65.1 | 78.0 | 101.6 | 207.8 | 459.7 | 766.1 | 2,594.8 | … | 165.7
Female | 74.8 | * | * | * | 20.7 | 32.2 | 32.0 | 54.7 | 148.7 | 321.4 | 813.2 | 1,990.0 | … | 122.9
Asian | 130.7 | 256.2 | * | * | 39.2 | 54.4 | 58.4 | 98.5 | 212.6 | 546.0 | 1,563.7 | 4,075.2 | … | 229.5
Male | 142.8 | * | * | * | 49.5 | 82.2 | 73.5 | 129.3 | 277.5 | 674.3 | 1,795.4 | 4,662.0 | … | 275.1
Female | 118.5 | 294.0 | * | * | * | * | * | 68.0 | 151.5 | 438.2 | 1,401.7 | 3,772.1 | … | 192.8
Black | 160.8 | 409.0 | 22.1 | 8.3 | 46.1 | 87.4 | 96.2 | 159.2 | 287.8 | 625.8 | 1,364.8 | 4,272.9 | … | 257.3
Male | 190.5 | 435.3 | 19.6 | 10.3 | 67.3 | 129.3 | 144.7 | 226.0 | 374.1 | 812.0 | 1,741.5 | 4,890.8 | … | 329.7
Female | 131.7 | 381.9 | 24.6 | 6.3 | 23.9 | 43.8 | 49.8 | 99.7 | 211.4 | 472.9 | 1,103.7 | 3,960.7 | … | 198.9
Native Hawaiian or Other Pacific Islander | 129.7 | * | * | * | 58.7 | 82.2 | 62.0 | 124.4 | 308.8 | 617.3 | 1,259.4 | 3,543.3 | … | 230.5
Male | 152.3 | * | * | * | * | 124.0 | * | 180.6 | 426.2 | 849.5 | * | * | … | 253.8
Female | 105.6 | * | * | * | * | * | * | * | * | * | 1,416.6 | 4,037.3 | … | 198.6
White | 478.3 | 513.3 | 23.1 | 14.4 | 79.8 | 152.3 | 212.1 | 351.9 | 754.5 | 1,629.3 | 3,917.7 | 11,724.9 | … | 655.0
Male | 530.0 | 554.9 | 24.3 | 15.9 | 117.7 | 225.0 | 292.0 | 463.0 | 972.2 | 2,031.8 | 4,649.1 | 13,064.0 | … | 798.1
Female | 424.9 | 470.1 | 21.9 | 12.8 | 40.1 | 74.0 | 123.4 | 234.9 | 536.4 | 1,278.0 | 3,385.4 | 11,009.4 | … | 530.6
Hispanic, two or more races^4^ | 124.5 | 419.8 | 21.3 | 6.0 | 35.4 | 72.6 | 95.1 | 146.5 | 317.9 | 622.1 | 1,458.5 | 4,279.4 | … | 258.4
Male | 140.9 | 426.1 | 23.8 | * | 49.7 | 103.6 | 121.9 | 178.7 | 402.7 | 798.7 | 1,781.7 | 4,558.6 | … | 311.6
Female | 107.9 | 413.2 | * | * | 20.7 | 40.4 | 68.3 | 115.4 | 241.0 | 477.6 | 1,227.3 | 4,128.4 | … | 214.1
Non-Hispanic, total | 1,110.7 | 579.5 | 29.9 | 16.0 | 80.9 | 168.8 | 269.8 | 480.5 | 1,031.3 | 2,018.4 | 4,791.1 | 14,669.3 | … | 820.4
Male | 1,171.2 | 627.5 | 33.6 | 18.0 | 114.0 | 230.5 | 347.5 | 595.3 | 1,272.6 | 2,460.9 | 5,612.7 | 16,453.0 | … | 977.4
Female | 1,051.8 | 529.1 | 26.1 | 13.9 | 46.3 | 105.3 | 191.7 | 366.1 | 799.6 | 1,623.7 | 4,136.8 | 13,698.3 | … | 686.9
Non-Hispanic, single race^3^ | 1,138.2 | 594.6 | 30.7 | 16.4 | 82.5 | 170.8 | 272.2 | 483.8 | 1,037.6 | 2,029.2 | 4,817.1 | 14,759.3 | … | 825.8
Male | 1,200.0 | 645.1 | 34.6 | 18.4 | 116.4 | 233.1 | 350.3 | 598.9 | 1,279.9 | 2,474.5 | 5,643.9 | 16,565.5 | … | 984.0
Female | 1,078.1 | 541.5 | 26.7 | 14.2 | 47.0 | 106.5 | 193.4 | 368.9 | 804.7 | 1,632.0 | 4,158.7 | 13,777.0 | … | 691.3
American Indian and Alaska Native | 975.4 | 833.5 | 60.0 | 33.7 | 182.9 | 466.8 | 734.7 | 1,003.1 | 1,467.7 | 2,198.2 | 4,134.7 | 8,138.4 | … | 947.9
Male | 1,062.4 | 932.8 | 58.9 | 36.6 | 242.2 | 581.5 | 930.0 | 1,209.6 | 1,741.4 | 2,515.4 | 4,365.5 | 7,885.2 | … | 1,084.3
Female | 890.2 | 729.8 | 61.1 | 30.6 | 121.6 | 347.7 | 538.3 | 800.0 | 1,216.1 | 1,925.8 | 3,946.3 | 8,292.0 | … | 816.1
Asian | 441.9 | 306.0 | 14.1 | 8.4 | 33.4 | 49.2 | 78.6 | 173.7 | 398.9 | 962.5 | 2,735.3 | 9,206.1 | … | 417.5
Male | 472.3 | 338.1 | 16.0 | 9.3 | 45.7 | 69.1 | 104.8 | 228.0 | 531.6 | 1,249.6 | 3,256.5 | 10,082.0 | … | 501.7
Female | 413.6 | 271.7 | 12.2 | 7.4 | 20.8 | 29.8 | 54.4 | 124.9 | 283.5 | 733.9 | 2,332.5 | 8,689.8 | … | 350.7
Black | 979.2 | 1,066.7 | 52.8 | 26.6 | 153.8 | 264.9 | 412.6 | 701.8 | 1,468.2 | 2,791.3 | 5,429.7 | 13,311.4 | … | 1,002.8
Male | 1,085.4 | 1,170.5 | 59.2 | 30.6 | 233.3 | 374.0 | 545.0 | 899.8 | 1,866.7 | 3,600.0 | 6,722.8 | 15,380.3 | … | 1,257.5
Female | 880.8 | 959.6 | 46.2 | 22.6 | 72.5 | 155.7 | 288.6 | 523.4 | 1,122.4 | 2,174.3 | 4,610.2 | 12,446.1 | … | 809.0
Native Hawaiian or Other Pacific Islander | 722.1 | 1,100.4 | 76.7 | 29.2 | 103.2 | 207.0 | 349.9 | 731.0 | 1,310.0 | 2,322.6 | 4,213.6 | 6,699.8 | … | 782.0
Male | 765.3 | 1,166.7 | * | * | 155.4 | 274.5 | 428.7 | 809.4 | 1,490.9 | 2,496.6 | 4,306.7 | 6,934.7 | … | 859.5
Female | 677.9 | 1,028.8 | * | * | 48.3 | 135.7 | 266.1 | 649.8 | 1,132.5 | 2,162.8 | 4,132.2 | 6,545.9 | … | 705.4
White | 1,247.6 | 472.8 | 25.4 | 14.0 | 67.2 | 156.8 | 259.7 | 468.0 | 1,007.3 | 1,993.4 | 4,883.6 | 15,332.2 | … | 822.2
Male | 1,299.7 | 509.9 | 28.8 | 15.7 | 91.3 | 211.4 | 331.3 | 573.3 | 1,233.6 | 2,409.1 | 5,695.4 | 17,191.0 | … | 972.1
Female | 1,196.1 | 433.8 | 21.8 | 12.2 | 41.8 | 99.7 | 185.4 | 359.1 | 783.8 | 1,611.3 | 4,220.1 | 14,301.9 | … | 692.7
Non-Hispanic, two or more races^4^ | 211.5 | 388.2 | 19.9 | 10.7 | 49.7 | 110.0 | 167.0 | 290.9 | 538.5 | 978.7 | 1,939.7 | 4,640.7 | … | 366.8
Male | 235.9 | 402.8 | 20.9 | 11.7 | 66.7 | 151.9 | 218.1 | 378.7 | 678.0 | 1,149.8 | 2,207.8 | 4,776.7 | … | 433.0
Female | 187.4 | 373.1 | 18.7 | 9.5 | 32.1 | 68.4 | 120.6 | 211.9 | 412.8 | 828.3 | 1,723.5 | 4,557.9 | … | 308.2

… Category not applicable.

– Quantity zero.

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

^1^Death rates for “Younger than 1” (based on population estimates) differ from infant mortality rates (based on live births); see Technical Notes.

^2^For method of computation, see Technical Notes.

^3^Only one race was reported on the death certificate; see Technical Notes.

^4^Two or more races were reported on the death certificate; see Technical Notes.

^5^Includes people of Hispanic origin of any race; see Technical Notes.

^6^Includes origin not stated or not classifiable; see Technical Notes.

^7^Data for age not stated included in “All ages” but not distributed among age groups.

^8^Includes deaths with origin not stated and origin not classifiable; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 3 Number of deaths and death rate by age, and age-adjusted death rate, by specified Hispanic origin and sex: United States, 2022

[Rates are per 100,000 population in specified group; age-adjusted rates are per 100,000 U.S. standard population; see Technical Notes in this report. Populations used for computing death rates for Hispanic total are postcensal estimates based on the 2010 census estimated as of July 1, 2022; populations used for computing death rates for Mexican, Puerto Rican, Cuban, Central American, South American, Dominican, and Other and unknown Hispanic are estimates based on the 2022 1-year American Community Survey adjusted to control totals. The control totals are 2010-based postcensal estimates for the United States for July 1, 2022; see Technical Notes. Hispanic origin is reported separately on the death certificate. People of Hispanic origin may be of any race. Data for Hispanic origin should be interpreted with caution because of inconsistencies between reporting Hispanic origin on death certificates and on censuses and surveys; see Technical Notes]

Hispanic origin and sex | All ages | Age group | | | | | | | | | | | Age not stated | Age-adjusted rate^2^
Hispanic origin and sex | All ages | Younger than 1^1^ | 1–4 | 5–14 | 15–24 | 25–34 | 35–44 | 45–54 | 55–64 | 65–74 | 75–84 | 85 and older | Age not stated | Age-adjusted rate^2^
| Number
Hispanic | 275,684 | 4,765 | 869 | 1,386 | 8,035 | 13,791 | 17,794 | 25,143 | 39,748 | 49,780 | 54,345 | 60,018 | 10 | …
Male | 155,240 | 2,612 | 466 | 787 | 6,040 | 10,542 | 12,875 | 16,955 | 25,576 | 28,932 | 27,163 | 23,283 | 9 | …
Female | 120,444 | 2,153 | 403 | 599 | 1,995 | 3,249 | 4,919 | 8,188 | 14,172 | 20,848 | 27,182 | 36,735 | 1 | …
Central American | 18,332 | 525 | 96 | 137 | 959 | 1,461 | 1,776 | 2,075 | 2,633 | 2,950 | 2,813 | 2,906 | 1 | …
Male | 10,625 | 290 | 49 | 77 | 775 | 1,203 | 1,382 | 1,506 | 1,674 | 1,577 | 1,215 | 876 | 1 | …
Female | 7,707 | 235 | 47 | 60 | 184 | 258 | 394 | 569 | 959 | 1,373 | 1,598 | 2,030 | – | …
Cuban | 20,303 | 100 | 19 | 27 | 132 | 285 | 396 | 744 | 1,917 | 2,971 | 5,141 | 8,570 | 1 | …
Male | 10,356 | 55 | 9 | 12 | 90 | 212 | 287 | 504 | 1,313 | 1,849 | 2,657 | 3,367 | 1 | …
Female | 9,947 | 45 | 10 | 15 | 42 | 73 | 109 | 240 | 604 | 1,122 | 2,484 | 5,203 | – | …
Dominican | 7,178 | 119 | 18 | 35 | 176 | 374 | 428 | 564 | 867 | 1,360 | 1,531 | 1,706 | – | …
Male | 3,721 | 65 | 9 | 23 | 125 | 276 | 293 | 347 | 520 | 762 | 752 | 549 | – | …
Female | 3,457 | 54 | 9 | 12 | 51 | 98 | 135 | 217 | 347 | 598 | 779 | 1,157 | – | …
Mexican | 148,306 | 2,725 | 476 | 812 | 4,785 | 7,853 | 10,384 | 14,945 | 22,734 | 27,693 | 27,718 | 28,177 | 4 | …
Male | 86,166 | 1,476 | 258 | 473 | 3,602 | 6,063 | 7,561 | 10,098 | 14,834 | 16,291 | 14,115 | 11,392 | 3 | …
Female | 62,140 | 1,249 | 218 | 339 | 1,183 | 1,790 | 2,823 | 4,847 | 7,900 | 11,402 | 13,603 | 16,785 | 1 | …
Puerto Rican | 33,536 | 418 | 91 | 115 | 605 | 1,365 | 1,952 | 2,932 | 4,928 | 6,443 | 7,445 | 7,241 | 1 | …
Male | 18,305 | 230 | 52 | 64 | 447 | 1,002 | 1,383 | 1,972 | 3,161 | 3,672 | 3,603 | 2,718 | 1 | …
Female | 15,231 | 188 | 39 | 51 | 158 | 363 | 569 | 960 | 1,767 | 2,771 | 3,842 | 4,523 | – | …
South American | 13,121 | 144 | 32 | 51 | 243 | 427 | 501 | 804 | 1,500 | 2,213 | 3,221 | 3,985 | – | …
Male | 6,627 | 77 | 18 | 26 | 173 | 330 | 340 | 488 | 881 | 1,241 | 1,581 | 1,472 | – | …
Female | 6,494 | 67 | 14 | 25 | 70 | 97 | 161 | 316 | 619 | 972 | 1,640 | 2,513 | – | …
Other and unknown Hispanic | 34,908 | 734 | 137 | 209 | 1,135 | 2,026 | 2,357 | 3,079 | 5,169 | 6,150 | 6,476 | 7,433 | 3 | …
Male | 19,440 | 419 | 71 | 112 | 828 | 1,456 | 1,629 | 2,040 | 3,193 | 3,540 | 3,240 | 2,909 | 3 | …
Female | 15,468 | 315 | 66 | 97 | 307 | 570 | 728 | 1,039 | 1,976 | 2,610 | 3,236 | 4,524 | – | …
| Rate^3^
Hispanic | 433.0 | 477.4 | 22.2 | 13.1 | 74.4 | 142.1 | 196.3 | 327.7 | 702.5 | 1,522.8 | 3,682.6 | 11,107.1 | … | 614.7
Male | 481.0 | 514.1 | 23.4 | 14.6 | 109.3 | 209.7 | 270.9 | 432.1 | 905.9 | 1,900.2 | 4,368.6 | 12,379.5 | … | 748.8
Female | 383.7 | 439.4 | 21.0 | 11.6 | 37.8 | 69.4 | 114.0 | 218.4 | 499.9 | 1,193.7 | 3,183.0 | 10,427.8 | … | 498.4
Central American | 280.7 | 479.1 | 21.2 | 12.6 | 86.4 | 135.4 | 167.8 | 272.0 | 525.0 | 1,182.2 | 3,017.9 | 9,982.8 | … | 517.9
Male | 316.4 | 539.5 | 21.3 | 14.0 | 132.9 | 213.5 | 237.8 | 373.1 | 681.5 | 1,493.6 | 3,793.3 | 10,109.6 | … | 632.0
Female | 242.9 | 420.8 | 21.1 | 11.2 | 34.9 | 50.1 | 82.6 | 158.4 | 374.9 | 953.9 | 2,612.0 | 9,929.1 | … | 421.8
Cuban | 833.6 | 430.8 | * | 10.3 | 49.1 | 81.8 | 118.4 | 221.2 | 574.2 | 1,424.0 | 3,827.0 | 12,658.8 | … | 587.4
Male | 838.0 | 491.9 | * | * | 64.6 | 119.3 | 157.9 | 275.2 | 783.7 | 1,854.5 | 4,593.3 | 14,416.6 | … | 717.2
Female | 829.0 | 374.1 | * | * | 32.4 | 42.8 | 71.4 | 156.7 | 363.1 | 1,030.0 | 3,247.5 | 11,733.0 | … | 478.2
Dominican | 299.5 | 291.9 | * | 9.3 | 48.3 | 97.4 | 126.7 | 196.4 | 381.7 | 946.5 | 2,454.9 | 9,554.7 | … | 427.1
Male | 327.5 | 268.0 | * | 12.3 | 68.7 | 144.7 | 181.3 | 275.0 | 540.0 | 1,280.9 | 3,252.6 | 10,828.4 | … | 547.3
Female | 274.3 | 327.0 | * | * | 28.0 | 50.7 | 76.6 | 134.7 | 265.2 | 710.2 | 1,985.0 | 9,049.7 | … | 346.9
Mexican | 396.4 | 496.7 | 20.4 | 12.3 | 70.4 | 136.1 | 197.0 | 337.6 | 753.0 | 1,623.5 | 3,865.6 | 12,105.9 | … | 649.5
Male | 450.8 | 533.7 | 21.6 | 14.0 | 103.7 | 202.4 | 274.0 | 441.4 | 967.2 | 1,973.3 | 4,545.0 | 13,203.5 | … | 779.8
Female | 339.6 | 459.2 | 19.2 | 10.5 | 35.6 | 64.5 | 112.4 | 226.6 | 531.8 | 1,295.4 | 3,346.5 | 11,459.3 | … | 531.2
Puerto Rican | 567.9 | 483.7 | 24.9 | 11.9 | 67.2 | 157.0 | 239.0 | 419.7 | 827.4 | 1,762.6 | 4,082.7 | 11,644.3 | … | 688.1
Male | 621.2 | 561.9 | 27.8 | 12.8 | 97.6 | 222.6 | 332.2 | 571.7 | 1,091.2 | 2,206.5 | 4,818.8 | 13,245.6 | … | 848.4
Female | 514.8 | 413.2 | 21.8 | 11.0 | 35.8 | 86.6 | 142.1 | 271.4 | 577.6 | 1,391.6 | 3,571.1 | 10,855.6 | … | 555.7
South American | 281.1 | 252.1 | 13.6 | 8.4 | 39.0 | 61.5 | 67.7 | 118.1 | 281.6 | 723.0 | 2,312.3 | 7,913.0 | … | 344.9
Male | 293.2 | 272.6 | * | 8.4 | 54.8 | 96.2 | 92.9 | 150.3 | 346.2 | 960.5 | 2,941.1 | 8,496.4 | … | 419.1
Female | 269.8 | 232.0 | * | 8.3 | 22.8 | 27.6 | 43.1 | 88.8 | 222.6 | 549.6 | 1,917.1 | 7,607.1 | … | 290.6
Other and unknown Hispanic | 830.5 | 1,117.8 | 52.3 | 31.3 | 159.4 | 356.7 | 438.1 | 674.8 | 1,195.4 | 2,055.3 | 4,381.6 | 13,669.9 | … | 904.1
Male | 913.4 | 1,380.1 | 55.1 | 31.9 | 226.3 | 481.3 | 576.7 | 875.4 | 1,501.8 | 2,581.3 | 5,095.9 | 14,083.8 | … | 1,083.6
Female | 745.6 | 892.2 | 49.6 | 30.7 | 88.6 | 214.7 | 284.9 | 465.5 | 899.1 | 1,610.3 | 3,842.3 | 13,416.4 | … | 735.2

… Category not applicable.

– Quantity zero.

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

^1^Death rates for ages younger than 1 (based on population estimates) differ from infant mortality rates (based on live births); see Technical Notes.

^2^For method of computation, see Technical Notes.

^3^Data for age not stated included in “All ages” but not distributed among age groups.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 4 Life expectancy at selected ages, by Hispanic origin and race and sex: United States, 2022

[Life expectancies are preliminary estimates and may change slightly when updated data become available. Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards]

Exact age | Total^1^ | | | Hispanic^23^ | | | Non-Hispanic^24^
Exact age | Total^1^ | | | Hispanic^23^ | | | American Indian and Alaska Native | | | Asian | | | Black | | | White
Exact age | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
0 | 77.5 | 74.8 | 80.2 | 80.0 | 77.0 | 82.8 | 67.8 | 64.5 | 71.3 | 84.4 | 82.3 | 86.3 | 72.8 | 69.1 | 76.5 | 77.5 | 75.1 | 80.1
1 | 76.9 | 74.3 | 79.6 | 79.4 | 76.4 | 82.2 | 67.4 | 64.2 | 70.8 | 83.7 | 81.6 | 85.6 | 72.6 | 68.9 | 76.3 | 76.9 | 74.4 | 79.4
5 | 73.0 | 70.4 | 75.7 | 75.4 | 72.5 | 78.3 | 63.6 | 60.4 | 67.0 | 79.8 | 77.7 | 81.6 | 68.8 | 65.1 | 72.4 | 72.9 | 70.5 | 75.5
10 | 68.0 | 65.4 | 70.7 | 70.5 | 67.5 | 73.3 | 58.7 | 55.5 | 62.1 | 74.8 | 72.7 | 76.6 | 63.8 | 60.1 | 67.5 | 68.0 | 65.6 | 70.5
15 | 63.1 | 60.5 | 65.8 | 65.5 | 62.6 | 68.4 | 53.8 | 50.6 | 57.2 | 69.8 | 67.8 | 71.7 | 58.9 | 55.2 | 62.6 | 63.0 | 60.6 | 65.6
20 | 58.3 | 55.7 | 60.9 | 60.7 | 57.8 | 63.5 | 49.2 | 46.1 | 52.6 | 64.9 | 62.9 | 66.7 | 54.3 | 50.7 | 57.7 | 58.2 | 55.8 | 60.7
25 | 53.5 | 51.1 | 56.0 | 56.0 | 53.2 | 58.6 | 44.8 | 41.8 | 48.0 | 60.1 | 58.0 | 61.8 | 49.8 | 46.4 | 53.0 | 53.4 | 51.1 | 55.8
30 | 48.9 | 46.6 | 51.3 | 51.3 | 48.7 | 53.8 | 40.7 | 38.0 | 43.6 | 55.2 | 53.2 | 56.9 | 45.3 | 42.2 | 48.3 | 48.8 | 46.6 | 51.0
35 | 44.3 | 42.1 | 46.5 | 46.7 | 44.2 | 49.0 | 36.9 | 34.3 | 39.6 | 50.4 | 48.4 | 52.0 | 40.9 | 38.0 | 43.7 | 44.2 | 42.1 | 46.3
40 | 39.8 | 37.7 | 41.9 | 42.1 | 39.8 | 44.2 | 33.4 | 31.0 | 35.8 | 45.6 | 43.7 | 47.1 | 36.6 | 33.8 | 39.3 | 39.7 | 37.7 | 41.7
45 | 35.3 | 33.4 | 37.3 | 37.6 | 35.4 | 39.5 | 29.8 | 27.8 | 31.9 | 40.8 | 38.9 | 42.2 | 32.5 | 29.8 | 34.9 | 35.2 | 33.3 | 37.1
50 | 30.9 | 29.1 | 32.8 | 33.1 | 31.0 | 34.9 | 26.7 | 24.9 | 28.4 | 36.1 | 34.3 | 37.4 | 28.4 | 25.9 | 30.6 | 30.8 | 29.1 | 32.6
55 | 26.7 | 25.0 | 28.4 | 28.7 | 26.8 | 30.3 | 23.5 | 21.9 | 25.0 | 31.4 | 29.8 | 32.7 | 24.4 | 22.1 | 26.4 | 26.6 | 25.0 | 28.2
60 | 22.7 | 21.1 | 24.2 | 24.5 | 22.7 | 25.9 | 20.6 | 19.3 | 21.8 | 26.9 | 25.4 | 28.0 | 20.8 | 18.6 | 22.6 | 22.6 | 21.1 | 24.0
65 | 18.9 | 17.5 | 20.2 | 20.5 | 19.0 | 21.7 | 17.8 | 16.8 | 18.7 | 22.5 | 21.2 | 23.4 | 17.4 | 15.5 | 19.0 | 18.8 | 17.5 | 20.0
70 | 15.3 | 14.2 | 16.3 | 16.7 | 15.4 | 17.7 | 14.9 | 14.2 | 15.5 | 18.4 | 17.2 | 19.1 | 14.4 | 12.8 | 15.6 | 15.2 | 14.1 | 16.2
75 | 12.0 | 11.0 | 12.8 | 13.2 | 12.1 | 13.9 | 12.4 | 11.9 | 12.6 | 14.5 | 13.6 | 15.0 | 11.5 | 10.2 | 12.4 | 11.8 | 10.9 | 12.6
80 | 8.9 | 8.1 | 9.5 | 10.0 | 9.1 | 10.4 | 9.9 | 9.6 | 10.0 | 10.8 | 10.1 | 11.1 | 8.9 | 7.8 | 9.5 | 8.8 | 8.0 | 9.4
85 | 6.4 | 5.8 | 6.8 | 7.2 | 6.5 | 7.4 | 7.9 | 7.7 | 7.8 | 7.7 | 7.2 | 7.8 | 6.6 | 5.8 | 7.0 | 6.3 | 5.7 | 6.7
90 | 4.4 | 3.9 | 4.6 | 5.0 | 4.4 | 5.0 | 6.2 | 6.1 | 6.0 | 5.1 | 4.8 | 5.1 | 4.8 | 4.2 | 5.0 | 4.3 | 3.8 | 4.5
95 | 3.0 | 2.7 | 3.1 | 3.4 | 3.0 | 3.3 | 4.8 | 4.9 | 4.6 | 3.4 | 3.2 | 3.2 | 3.4 | 3.1 | 3.5 | 2.9 | 2.6 | 3.0
100 | 2.1 | 1.9 | 2.2 | 2.4 | 2.2 | 2.3 | 3.9 | 4.0 | 3.6 | 2.3 | 2.2 | 2.1 | 2.5 | 2.3 | 2.5 | 2.0 | 1.8 | 2.1

^1^Includes origins and races not shown separately; see Technical Notes in this report.

^2^Based on death rates adjusted for Hispanic-origin and race misclassification on death certificates; see Technical Notes.

^3^Includes persons of Hispanic origin of any race; see Technical Notes.

^4^Only one race was reported on the death certificate; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 5 Life expectancy at birth, by Hispanic origin and race and sex: United States, 1940, 1950, 1960, 1970, 1980, 1990, and 2000–2022

Hispanic origin and race and year | Both sexes | Male | Female
All origins and races^1^
2022^2^ | 77.5 | 74.8 | 80.2
2021^2^ | 76.4 | 73.5 | 79.3
2020^2^ | 77.0 | 74.2 | 79.9
2019^23^ | 78.8 | 76.3 | 81.4
2018^2^ | 78.7 | 76.2 | 81.2
2017^2^ | 78.6 | 76.1 | 81.1
2016^2^ | 78.7 | 76.2 | 81.1
2015^2^ | 78.7 | 76.3 | 81.1
2014^2^ | 78.9 | 76.5 | 81.3
2013^2^ | 78.8 | 76.4 | 81.2
2012^2^ | 78.8 | 76.4 | 81.2
2011^2^ | 78.7 | 76.3 | 81.1
2010^2^ | 78.7 | 76.2 | 81.0
2009^2^ | 78.5 | 76.0 | 80.9
2008^2^ | 78.2 | 75.6 | 80.6
2007 | 78.1 | 75.5 | 80.6
2006 | 77.8 | 75.2 | 80.3
2005 | 77.6 | 75.0 | 80.1
2004 | 77.6 | 75.0 | 80.1
2003 | 77.2 | 74.5 | 79.7
2002 | 77.0 | 74.4 | 79.6
2001 | 77.0 | 74.3 | 79.5
2000 | 76.8 | 74.1 | 79.3
1990 | 75.4 | 71.8 | 78.8
1980 | 73.7 | 70.0 | 77.4
1970 | 70.8 | 67.1 | 74.7
1960 | 69.7 | 66.6 | 73.1
1950 | 68.2 | 65.6 | 71.1
1940 | 62.9 | 60.8 | 65.2
Hispanic^4–6^
2022^2^ | 80.0 | 77.0 | 82.8
2021^2^ | 77.8 | 74.6 | 81.1
2020^2^ | 77.9 | 74.6 | 81.3
2019^23^ | 81.9 | 79.1 | 84.4
2018^2^ | 81.8 | 79.1 | 84.3
2017^2^ | 81.8 | 79.1 | 84.3
2016^2^ | 81.8 | 79.1 | 84.3
2015^27^ | 81.9 | 79.3 | 84.3
2014^2^ | 82.1 | 79.4 | 84.5
2013^2^ | 81.9 | 79.2 | 84.2
2012^2^ | 81.9 | 79.3 | 84.3
2011^2^ | 81.8 | 79.2 | 84.2
2010^2^ | 81.7 | 78.8 | 84.3
2009^2^ | 81.1 | 78.4 | 83.5
2008^2^ | 80.8 | 78.0 | 83.3
2007 | 80.7 | 77.8 | 83.2
2006 | 80.3 | 77.5 | 82.9
Non-Hispanic, single race^6,8^
American Indian and Alaska Native:
2022^2^ | 67.8 | 64.5 | 71.3
2021^2^ | 65.6 | 62.2 | 69.2
2020^2^ | 67.1 | 63.8 | 70.7
2019^23^ | 71.8 | 68.6 | 75.0
2018^2^ | --- | --- | ---
Asian:
2022^2^ | 84.4 | 82.3 | 86.3
2021^2^ | 83.5 | 81.2 | 85.6
2020^2^ | 83.6 | 81.1 | 85.9
2019^23^ | 85.6 | 83.5 | 87.4
2018^2^ | --- | --- | ---
Black:
2022^2^ | 72.8 | 69.1 | 76.5
2021^2^ | 71.2 | 67.6 | 75.0
2020^2^ | 71.5 | 67.8 | 75.4
2019^23^ | 74.8 | 71.3 | 78.1
2018^2^ | 74.7 | 71.3 | 78.0
White:
2022^2^ | 77.5 | 75.1 | 80.1
2021^2^ | 76.7 | 74.0 | 79.5
2020^2^ | 77.4 | 74.8 | 80.1
2019^23^ | 78.8 | 76.3 | 81.3
2018^2^ | 78.6 | 76.2 | 81.1

--- Data not available.

^1^Includes origins and races not shown separately; see Technical Notes in this report.

^2^Life expectancies for 2008–2022 were calculated using newly revised methodology described in the Technical Notes.

^3^Life expectancies were updated using final data; therefore, data may differ from preliminary data previously published; see Technical Notes.

^4^Includes persons of Hispanic origin of any race. The Hispanic-origin category is consistent with 1997 OMB standards; see Technical Notes.

^5^Data by Hispanic origin available beginning with data year 2006.

^6^Based on death rate adjusted for race and Hispanic-origin misclassification; see Technical Notes.

^7^Life expectancies were revised using updated Medicare data; as a result, data may differ from those previously published; see Technical Notes.

^8^Only one race was reported on the death certificate. Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 6 Death rate by age, and age-adjusted death rate, for the 15 leading causes of death in 2022, dementia-related causes, drug-induced causes, alcohol-induced causes, and injury by firearms: United States, 1999–2022

[Rates are on an annual basis per 100,000 population in specified group; age-adjusted rates are per 100,000 U.S. standard population; see Technical Notes in this report. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10); see Technical Notes]

Cause of death (based on ICD–10) and year | All ages^1^ | Age group | | | | | | | | | | | Age-adjusted rate^3^
Cause of death (based on ICD–10) and year | All ages^1^ | Younger than 1^2^ | 1–4 | 5–14 | 15–24 | 25–34 | 35–44 | 45–54 | 55–64 | 65–74 | 75–84 | 85 and older | Age-adjusted rate^3^
All causes
2022 | 984.1 | 558.0 | 28.0 | 15.3 | 79.5 | 163.4 | 255.4 | 453.3 | 992.1 | 1,978.7 | 4,708.2 | 14,389.6 | 798.8
2021 | 1,043.8 | 558.8 | 25.0 | 14.3 | 88.9 | 180.8 | 287.9 | 531.0 | 1,117.1 | 2,151.3 | 5,119.4 | 15,743.3 | 879.7
2020 | 1,027.0 | 524.3 | 22.7 | 13.7 | 84.2 | 159.5 | 248.0 | 473.5 | 1,038.9 | 2,072.3 | 4,997.0 | 15,210.9 | 835.4
2019 | 869.7 | 553.0 | 23.3 | 13.4 | 69.7 | 128.8 | 199.2 | 392.4 | 883.3 | 1,764.6 | 4,308.3 | 13,228.6 | 715.2
2018 | 867.8 | 557.8 | 24.0 | 13.3 | 70.2 | 128.8 | 194.7 | 395.9 | 886.7 | 1,783.3 | 4,386.1 | 13,450.7 | 723.6
2017 | 863.8 | 567.0 | 24.3 | 13.6 | 74.0 | 132.8 | 195.2 | 401.5 | 885.8 | 1,790.9 | 4,472.6 | 13,573.6 | 731.9
2016 | 849.3 | 583.4 | 25.3 | 13.4 | 74.9 | 129.0 | 192.2 | 405.5 | 883.8 | 1,788.6 | 4,474.8 | 13,392.1 | 728.8
2015 | 844.0 | 589.6 | 24.9 | 13.2 | 69.5 | 116.7 | 180.1 | 404.0 | 875.3 | 1,796.8 | 4,579.2 | 13,673.9 | 733.1
2014 | 823.7 | 588.0 | 24.0 | 12.7 | 65.5 | 108.4 | 175.2 | 404.8 | 870.3 | 1,786.3 | 4,564.2 | 13,407.9 | 724.6
2013 | 821.5 | 594.7 | 25.5 | 13.0 | 64.8 | 106.1 | 172.0 | 406.1 | 860.0 | 1,802.1 | 4,648.1 | 13,660.4 | 731.9
2012 | 810.2 | 599.3 | 26.3 | 12.6 | 66.4 | 105.4 | 170.7 | 405.4 | 854.2 | 1,802.5 | 4,674.5 | 13,678.6 | 732.8
2011 | 807.3 | 600.1 | 26.3 | 13.2 | 67.7 | 104.7 | 172.0 | 409.8 | 849.4 | 1,846.2 | 4,753.0 | 13,779.3 | 741.3
2010 | 799.5 | 623.4 | 26.5 | 12.9 | 67.7 | 102.9 | 170.5 | 407.1 | 851.9 | 1,875.1 | 4,790.2 | 13,934.3 | 747.0
2009 | 794.5 | 659.7 | 27.4 | 13.8 | 69.8 | 104.4 | 180.0 | 418.1 | 856.7 | 1,888.7 | 4,820.2 | 13,660.1 | 749.6
2008 | 812.9 | 678.9 | 29.3 | 13.9 | 74.2 | 105.1 | 181.0 | 419.6 | 867.1 | 1,958.4 | 4,998.1 | 14,332.4 | 774.9
2007 | 804.6 | 702.5 | 29.4 | 15.2 | 78.8 | 107.2 | 186.0 | 420.3 | 866.7 | 1,976.0 | 4,987.1 | 14,160.9 | 775.3
2006 | 813.1 | 705.8 | 29.1 | 15.2 | 81.4 | 109.0 | 192.0 | 427.5 | 881.3 | 2,031.4 | 5,096.1 | 14,426.7 | 791.8
2005 | 828.4 | 710.2 | 29.9 | 16.3 | 80.7 | 106.8 | 194.9 | 431.9 | 898.5 | 2,109.7 | 5,251.8 | 14,982.4 | 815.0
2004 | 818.8 | 695.9 | 30.3 | 16.7 | 79.7 | 104.1 | 194.9 | 426.8 | 903.2 | 2,141.0 | 5,267.4 | 14,777.6 | 813.7
2003 | 843.9 | 704.9 | 31.8 | 16.9 | 81.1 | 105.2 | 202.6 | 433.1 | 937.3 | 2,235.0 | 5,451.3 | 15,401.4 | 843.5
2002 | 849.5 | 709.5 | 31.4 | 17.4 | 80.9 | 105.1 | 204.2 | 431.0 | 948.7 | 2,300.3 | 5,543.8 | 15,589.5 | 855.9
2001 | 848.0 | 687.0 | 33.4 | 17.2 | 80.2 | 105.6 | 203.5 | 426.7 | 972.5 | 2,344.2 | 5,573.7 | 15,432.6 | 858.8
2000 | 854.0 | 736.7 | 32.4 | 18.0 | 79.9 | 101.4 | 198.9 | 425.6 | 992.2 | 2,399.1 | 5,666.5 | 15,524.4 | 869.0
1999 | 857.0 | 736.0 | 34.2 | 18.6 | 79.3 | 102.2 | 198.0 | 418.2 | 1,005.0 | 2,457.3 | 5,714.5 | 15,554.6 | 875.6
Diseases of heart (I00–I09,I11,I13,I20–I51)
2022 | 210.9 | 6.5 | 0.7 | 0.5 | 1.9 | 8.3 | 28.1 | 79.9 | 203.7 | 415.7 | 1,016.6 | 3,835.8 | 167.2
2021 | 209.6 | 7.4 | 0.8 | 0.5 | 2.2 | 9.1 | 29.4 | 84.9 | 208.7 | 416.6 | 1,044.2 | 4,078.7 | 173.8
2020 | 211.5 | 6.5 | 0.7 | 0.4 | 2.0 | 8.6 | 28.9 | 84.6 | 208.8 | 414.2 | 1,017.2 | 3,822.1 | 168.2
2019 | 200.8 | 7.1 | 0.8 | 0.4 | 2.0 | 7.6 | 25.2 | 76.2 | 190.4 | 388.8 | 991.2 | 3,798.3 | 161.5
2018 | 200.3 | 7.5 | 0.7 | 0.4 | 2.1 | 7.8 | 25.5 | 77.4 | 191.7 | 392.4 | 1,008.3 | 3,844.8 | 163.6
2017 | 198.8 | 7.7 | 0.8 | 0.4 | 2.1 | 8.1 | 25.4 | 77.1 | 190.7 | 392.9 | 1,028.4 | 3,882.9 | 165.0
2016 | 196.6 | 7.4 | 0.7 | 0.5 | 2.2 | 7.7 | 25.9 | 79.5 | 189.6 | 392.5 | 1,037.1 | 3,873.4 | 165.5
2015 | 197.2 | 7.3 | 0.9 | 0.5 | 2.3 | 8.0 | 25.6 | 79.3 | 188.1 | 389.5 | 1,071.6 | 3,986.5 | 168.5
2014 | 192.7 | 8.0 | 0.9 | 0.5 | 2.2 | 7.7 | 25.6 | 80.1 | 185.8 | 385.2 | 1,070.2 | 3,920.9 | 167.0
2013 | 193.3 | 7.8 | 1.1 | 0.4 | 2.1 | 7.6 | 25.6 | 80.3 | 184.6 | 390.3 | 1,095.1 | 4,013.9 | 169.8
2012 | 191.0 | 8.5 | 1.0 | 0.4 | 2.2 | 7.6 | 25.9 | 79.7 | 184.6 | 388.3 | 1,103.7 | 4,046.1 | 170.5
2011 | 191.5 | 7.7 | 1.0 | 0.5 | 2.3 | 7.9 | 26.2 | 80.7 | 183.2 | 399.0 | 1,134.7 | 4,111.6 | 173.7
2010 | 193.6 | 8.3 | 1.0 | 0.5 | 2.4 | 7.8 | 25.8 | 81.6 | 186.6 | 409.2 | 1,172.0 | 4,285.2 | 179.1
2009 | 195.4 | 9.6 | 0.9 | 0.5 | 2.4 | 7.8 | 26.7 | 82.3 | 190.0 | 422.8 | 1,210.8 | 4,316.9 | 182.8
2008 | 202.8 | 9.6 | 1.2 | 0.6 | 2.5 | 8.1 | 26.9 | 85.2 | 195.3 | 441.4 | 1,271.7 | 4,598.4 | 192.1
2007 | 204.5 | 10.2 | 1.1 | 0.6 | 2.5 | 8.1 | 27.7 | 85.2 | 197.8 | 454.8 | 1,308.6 | 4,668.1 | 196.1
2006 | 211.7 | 8.6 | 1.0 | 0.6 | 2.5 | 8.4 | 28.5 | 88.0 | 205.1 | 483.0 | 1,378.0 | 4,877.6 | 205.5
2005 | 220.7 | 8.9 | 0.9 | 0.6 | 2.6 | 8.3 | 29.2 | 89.7 | 212.8 | 512.3 | 1,458.5 | 5,188.3 | 216.8
2004 | 222.8 | 10.5 | 1.2 | 0.6 | 2.5 | 8.1 | 29.5 | 90.2 | 217.1 | 535.7 | 1,504.1 | 5,233.8 | 221.6
2003 | 236.1 | 11.0 | 1.2 | 0.6 | 2.7 | 8.3 | 30.8 | 92.4 | 232.3 | 579.8 | 1,607.7 | 5,570.7 | 236.3
2002 | 242.3 | 12.7 | 1.1 | 0.6 | 2.5 | 8.0 | 30.7 | 93.9 | 240.5 | 612.0 | 1,673.2 | 5,726.3 | 244.6
2001 | 245.7 | 11.9 | 1.5 | 0.7 | 2.5 | 8.0 | 29.6 | 92.4 | 248.9 | 632.6 | 1,723.0 | 5,784.1 | 249.5
2000 | 252.6 | 13.0 | 1.2 | 0.7 | 2.6 | 7.4 | 29.2 | 94.2 | 261.2 | 665.6 | 1,780.3 | 5,926.1 | 257.6
1999 | 259.9 | 13.8 | 1.2 | 0.7 | 2.8 | 7.6 | 30.2 | 95.7 | 269.9 | 701.7 | 1,849.9 | 6,063.0 | 266.5
Malignant neoplasms (C00–C97)
2022 | 182.5 | 1.1 | 1.8 | 2.0 | 3.2 | 8.0 | 25.6 | 82.5 | 249.8 | 529.4 | 979.3 | 1,573.5 | 142.3
2021 | 182.4 | 1.5 | 1.8 | 1.9 | 3.1 | 7.9 | 25.8 | 82.5 | 252.4 | 532.1 | 1,017.2 | 1,712.9 | 146.6
2020 | 182.8 | 1.4 | 2.0 | 1.9 | 3.1 | 7.8 | 25.5 | 85.7 | 260.0 | 539.1 | 990.0 | 1,538.1 | 144.1
2019 | 182.7 | 1.5 | 1.8 | 1.9 | 3.3 | 7.8 | 25.7 | 87.1 | 263.3 | 543.3 | 1,005.9 | 1,571.0 | 146.2
2018 | 183.2 | 1.3 | 2.0 | 2.1 | 3.2 | 8.1 | 25.8 | 89.6 | 269.6 | 554.4 | 1,031.5 | 1,577.7 | 149.1
2017 | 183.9 | 1.4 | 2.0 | 2.1 | 3.2 | 8.0 | 26.7 | 92.7 | 273.4 | 567.5 | 1,060.2 | 1,600.3 | 152.5
2016 | 185.1 | 1.7 | 2.4 | 2.1 | 3.3 | 8.5 | 26.9 | 96.5 | 280.6 | 578.3 | 1,081.7 | 1,620.3 | 155.8
2015 | 185.4 | 1.3 | 2.2 | 2.1 | 3.4 | 8.4 | 26.9 | 99.7 | 284.1 | 594.3 | 1,100.8 | 1,628.6 | 158.5
2014 | 185.6 | 1.3 | 2.0 | 2.1 | 3.6 | 8.3 | 27.8 | 103.2 | 287.6 | 603.1 | 1,125.9 | 1,632.9 | 161.2
2013 | 185.0 | 1.6 | 2.1 | 2.2 | 3.4 | 8.6 | 28.1 | 105.5 | 288.2 | 616.9 | 1,139.4 | 1,635.4 | 163.2
2012 | 185.6 | 1.6 | 2.4 | 2.2 | 3.6 | 8.7 | 28.0 | 108.5 | 293.2 | 632.2 | 1,161.7 | 1,658.9 | 166.5
2011 | 185.1 | 1.8 | 2.2 | 2.1 | 3.7 | 8.4 | 28.8 | 109.3 | 295.8 | 647.6 | 1,179.1 | 1,676.2 | 169.0
2010 | 186.2 | 1.6 | 2.1 | 2.2 | 3.7 | 8.8 | 28.8 | 111.6 | 300.1 | 666.1 | 1,202.2 | 1,729.5 | 172.8
2009 | 185.0 | 1.8 | 2.2 | 2.2 | 3.8 | 9.0 | 30.2 | 112.8 | 301.7 | 668.2 | 1,213.0 | 1,699.3 | 173.5
2008 | 186.0 | 1.7 | 2.4 | 2.2 | 3.8 | 8.8 | 30.1 | 113.4 | 304.7 | 688.4 | 1,230.9 | 1,724.6 | 176.4
2007 | 186.9 | 1.7 | 2.3 | 2.4 | 3.8 | 8.7 | 31.0 | 114.2 | 311.4 | 702.9 | 1,250.1 | 1,739.4 | 179.3
2006 | 187.6 | 1.9 | 2.4 | 2.2 | 3.8 | 9.3 | 32.2 | 116.3 | 317.7 | 716.3 | 1,259.2 | 1,748.3 | 181.8
2005 | 189.3 | 1.9 | 2.4 | 2.5 | 4.0 | 9.2 | 33.5 | 118.6 | 323.9 | 733.2 | 1,272.8 | 1,778.2 | 185.1
2004 | 189.2 | 1.8 | 2.5 | 2.5 | 4.1 | 9.3 | 33.6 | 119.0 | 330.8 | 746.8 | 1,278.6 | 1,767.4 | 186.8
2003 | 192.0 | 1.9 | 2.5 | 2.6 | 4.0 | 9.5 | 35.1 | 122.1 | 341.6 | 763.5 | 1,299.7 | 1,792.3 | 190.9
2002 | 193.7 | 1.9 | 2.6 | 2.6 | 4.2 | 9.8 | 36.0 | 124.1 | 349.7 | 787.2 | 1,308.8 | 1,812.4 | 194.3
2001 | 194.3 | 1.6 | 2.7 | 2.4 | 4.2 | 10.1 | 36.8 | 125.8 | 359.4 | 799.7 | 1,313.7 | 1,802.9 | 196.5
2000 | 196.5 | 2.4 | 2.7 | 2.5 | 4.4 | 9.8 | 36.6 | 127.5 | 366.7 | 816.3 | 1,335.6 | 1,819.4 | 199.6
1999 | 197.0 | 1.8 | 2.7 | 2.5 | 4.5 | 10.0 | 37.1 | 127.6 | 374.6 | 827.1 | 1,331.5 | 1,805.8 | 200.8
Accidents (unintentional injuries) (V01–X59,Y85–Y86)
2022 | 68.1 | 36.8 | 8.7 | 4.0 | 33.1 | 72.7 | 84.6 | 77.6 | 80.8 | 68.5 | 127.8 | 417.4 | 64.0
2021 | 67.8 | 36.6 | 8.5 | 4.2 | 36.7 | 75.7 | 84.0 | 77.2 | 78.2 | 64.7 | 126.8 | 446.0 | 64.7
2020 | 61.0 | 32.0 | 7.4 | 3.8 | 35.5 | 68.0 | 73.7 | 68.9 | 68.2 | 57.2 | 113.3 | 383.6 | 57.6
2019 | 52.7 | 33.5 | 7.3 | 3.6 | 27.5 | 53.4 | 57.8 | 57.1 | 58.6 | 54.5 | 115.5 | 377.4 | 49.3
2018 | 51.1 | 30.4 | 7.7 | 3.5 | 28.0 | 53.9 | 54.9 | 55.4 | 56.0 | 52.3 | 111.3 | 368.6 | 48.0
2017 | 52.2 | 33.4 | 7.9 | 3.8 | 31.1 | 56.6 | 55.8 | 57.7 | 55.7 | 50.7 | 113.3 | 374.9 | 49.4
2016 | 49.9 | 30.7 | 7.9 | 4.0 | 31.9 | 53.7 | 51.8 | 54.6 | 52.7 | 49.1 | 110.7 | 365.7 | 47.4
2015 | 45.6 | 32.5 | 7.8 | 3.7 | 28.5 | 44.8 | 43.9 | 49.8 | 47.7 | 47.0 | 111.5 | 364.5 | 43.2
2014 | 42.6 | 29.4 | 7.6 | 3.6 | 26.8 | 39.8 | 39.6 | 47.4 | 44.9 | 45.1 | 108.7 | 349.1 | 40.5
2013 | 41.3 | 29.3 | 8.3 | 3.7 | 26.4 | 37.8 | 38.0 | 46.5 | 43.4 | 43.5 | 107.4 | 340.0 | 39.4
2012 | 40.7 | 29.6 | 8.4 | 3.8 | 27.1 | 37.5 | 37.1 | 46.1 | 41.0 | 44.0 | 107.8 | 336.9 | 39.1
2011 | 40.6 | 29.1 | 8.5 | 4.0 | 28.2 | 37.1 | 37.5 | 46.4 | 39.8 | 44.5 | 107.0 | 333.8 | 39.1
2010 | 39.1 | 28.1 | 8.6 | 4.0 | 28.3 | 35.5 | 36.0 | 43.7 | 38.4 | 43.3 | 106.1 | 328.4 | 38.0
2009 | 38.5 | 29.5 | 9.0 | 4.1 | 28.6 | 34.5 | 36.4 | 44.5 | 36.5 | 42.1 | 103.5 | 310.9 | 37.5
2008 | 40.1 | 31.8 | 9.1 | 4.6 | 32.5 | 36.3 | 38.1 | 45.8 | 37.4 | 43.9 | 105.7 | 318.3 | 39.2
2007 | 41.1 | 31.0 | 9.9 | 5.4 | 36.8 | 37.7 | 39.6 | 46.2 | 36.8 | 44.4 | 105.0 | 313.6 | 40.4
2006 | 40.8 | 28.4 | 10.1 | 5.6 | 37.9 | 38.0 | 40.5 | 45.5 | 35.8 | 43.8 | 104.7 | 299.2 | 40.2
2005 | 39.9 | 27.0 | 10.5 | 5.9 | 37.1 | 35.7 | 38.9 | 43.2 | 35.4 | 45.7 | 106.0 | 303.5 | 39.5
2004 | 38.3 | 26.2 | 10.4 | 6.5 | 36.8 | 33.2 | 37.6 | 40.7 | 32.9 | 43.5 | 103.6 | 295.8 | 38.1
2003 | 37.7 | 23.8 | 11.0 | 6.4 | 36.9 | 32.0 | 38.0 | 38.8 | 32.7 | 43.7 | 101.6 | 294.3 | 37.6
2002 | 37.1 | 23.9 | 10.6 | 6.6 | 37.7 | 31.9 | 37.4 | 36.7 | 31.3 | 44.0 | 101.1 | 289.6 | 37.1
2001 | 35.6 | 24.3 | 11.2 | 6.9 | 35.8 | 30.0 | 35.4 | 33.9 | 30.5 | 42.6 | 100.7 | 282.2 | 35.7
2000 | 34.8 | 23.1 | 11.9 | 7.3 | 36.0 | 29.5 | 34.1 | 32.6 | 30.9 | 41.9 | 95.1 | 273.5 | 34.9
1999 | 35.1 | 22.3 | 12.4 | 7.6 | 35.3 | 29.6 | 33.8 | 31.8 | 30.6 | 44.6 | 100.5 | 282.4 | 35.3
COVID-19 (U07.1)^4^
2022 | 56.0 | 3.8 | 0.7 | 0.3 | 1.0 | 3.6 | 8.8 | 23.9 | 57.6 | 124.5 | 292.2 | 818.2 | 44.5
2021 | 125.6 | 2.6 | 0.4 | 0.3 | 3.3 | 13.5 | 36.9 | 90.6 | 172.2 | 305.1 | 609.7 | 1,354.4 | 104.1
2020 | 106.5 | 0.9 | * | 0.1 | 1.2 | 4.9 | 14.4 | 42.0 | 99.3 | 234.3 | 589.8 | 1,645.0 | 85.0
Cerebrovascular diseases (I60–I69)
2022 | 49.6 | 2.4 | 0.3 | 0.2 | 0.4 | 1.3 | 4.9 | 13.8 | 33.7 | 84.0 | 265.0 | 1,043.9 | 39.5
2021 | 49.1 | 2.7 | 0.4 | 0.2 | 0.4 | 1.4 | 5.0 | 14.1 | 34.2 | 84.1 | 274.8 | 1,111.1 | 41.1
2020 | 48.6 | 2.8 | 0.4 | 0.2 | 0.4 | 1.3 | 4.8 | 14.1 | 33.4 | 81.0 | 262.9 | 1,017.9 | 38.8
2019 | 45.7 | 2.7 | 0.3 | 0.2 | 0.4 | 1.3 | 4.2 | 12.6 | 30.5 | 76.4 | 254.2 | 977.3 | 37.0
2018 | 45.2 | 2.5 | 0.3 | 0.2 | 0.3 | 1.2 | 4.1 | 12.3 | 30.3 | 76.8 | 256.0 | 984.3 | 37.1
2017 | 44.9 | 2.5 | 0.4 | 0.2 | 0.4 | 1.3 | 4.4 | 12.3 | 30.3 | 76.4 | 263.1 | 993.5 | 37.6
2016 | 44.0 | 3.1 | 0.3 | 0.2 | 0.3 | 1.3 | 4.6 | 12.5 | 29.7 | 76.0 | 265.5 | 972.9 | 37.3
2015 | 43.7 | 2.2 | 0.3 | 0.2 | 0.4 | 1.3 | 4.4 | 12.3 | 29.6 | 75.5 | 273.0 | 975.8 | 37.6
2014 | 41.7 | 2.4 | 0.2 | 0.2 | 0.4 | 1.3 | 4.3 | 12.3 | 29.3 | 74.5 | 265.7 | 929.7 | 36.5
2013 | 40.8 | 2.7 | 0.2 | 0.2 | 0.3 | 1.2 | 4.2 | 12.4 | 28.9 | 74.2 | 268.9 | 906.0 | 36.2
2012 | 40.9 | 2.6 | 0.3 | 0.2 | 0.4 | 1.3 | 4.3 | 12.8 | 28.7 | 75.7 | 272.2 | 931.2 | 36.9
2011 | 41.4 | 3.4 | 0.3 | 0.2 | 0.4 | 1.3 | 4.2 | 12.8 | 29.4 | 78.2 | 285.4 | 943.7 | 37.9
2010 | 41.9 | 3.3 | 0.3 | 0.2 | 0.4 | 1.3 | 4.6 | 13.1 | 29.3 | 81.7 | 288.3 | 993.8 | 39.1
2009 | 42.0 | 3.7 | 0.3 | 0.2 | 0.4 | 1.3 | 4.6 | 13.7 | 29.7 | 82.8 | 294.9 | 992.2 | 39.6
2008 | 44.1 | 3.4 | 0.4 | 0.2 | 0.4 | 1.3 | 4.8 | 13.7 | 30.6 | 87.3 | 313.3 | 1,071.0 | 42.1
2007 | 45.1 | 3.2 | 0.3 | 0.2 | 0.5 | 1.3 | 5.0 | 14.5 | 31.7 | 91.4 | 320.8 | 1,110.7 | 43.5
2006 | 46.0 | 3.5 | 0.3 | 0.2 | 0.5 | 1.3 | 5.1 | 14.6 | 32.9 | 94.9 | 333.9 | 1,131.7 | 44.8
2005 | 48.6 | 3.1 | 0.4 | 0.2 | 0.5 | 1.4 | 5.2 | 15.0 | 32.7 | 99.8 | 358.4 | 1,239.7 | 48.0
2004 | 51.3 | 3.2 | 0.3 | 0.2 | 0.5 | 1.4 | 5.4 | 14.8 | 34.0 | 106.6 | 385.6 | 1,331.9 | 51.2
2003 | 54.4 | 2.5 | 0.3 | 0.2 | 0.5 | 1.5 | 5.6 | 15.0 | 35.5 | 111.9 | 409.8 | 1,446.0 | 54.6
2002 | 56.6 | 3.0 | 0.3 | 0.2 | 0.4 | 1.4 | 5.4 | 15.1 | 37.1 | 119.6 | 430.0 | 1,520.1 | 57.2
2001 | 57.4 | 2.7 | 0.4 | 0.2 | 0.5 | 1.5 | 5.5 | 15.0 | 38.3 | 122.9 | 443.3 | 1,532.0 | 58.4
2000 | 59.6 | 3.3 | 0.3 | 0.2 | 0.5 | 1.5 | 5.8 | 16.0 | 41.0 | 128.6 | 461.3 | 1,589.2 | 60.9
1999 | 60.0 | 2.7 | 0.3 | 0.2 | 0.5 | 1.4 | 5.7 | 15.2 | 40.6 | 130.8 | 469.8 | 1,614.8 | 61.6
Chronic lower respiratory diseases (J40–J47)
2022 | 44.2 | * | 0.3 | 0.3 | 0.4 | 0.8 | 1.7 | 7.4 | 40.7 | 114.6 | 283.9 | 575.8 | 34.3
2021 | 42.9 | * | 0.2 | 0.2 | 0.4 | 0.8 | 1.7 | 7.8 | 41.2 | 112.7 | 285.9 | 600.6 | 34.7
2020 | 46.3 | * | * | 0.4 | 0.5 | 0.9 | 1.9 | 8.8 | 44.4 | 118.5 | 300.1 | 612.6 | 36.4
2019 | 47.8 | * | 0.2 | 0.4 | 0.4 | 0.8 | 1.6 | 8.8 | 44.2 | 124.6 | 318.0 | 654.3 | 38.2
2018 | 48.7 | * | 0.3 | 0.3 | 0.4 | 0.7 | 1.6 | 9.1 | 44.5 | 128.6 | 335.7 | 682.4 | 39.7
2017 | 49.2 | * | 0.2 | 0.3 | 0.4 | 0.7 | 1.7 | 9.4 | 44.4 | 133.8 | 347.6 | 700.6 | 40.9
2016 | 47.8 | 0.7 | 0.3 | 0.3 | 0.5 | 0.8 | 1.7 | 10.1 | 43.0 | 134.1 | 347.2 | 676.9 | 40.6
2015 | 48.2 | 0.7 | 0.3 | 0.4 | 0.5 | 0.7 | 1.7 | 10.1 | 42.7 | 136.6 | 357.9 | 705.1 | 41.6
2014 | 46.1 | * | 0.3 | 0.3 | 0.4 | 0.8 | 1.9 | 10.1 | 41.2 | 134.9 | 349.0 | 670.5 | 40.5
2013 | 47.2 | 0.6 | 0.4 | 0.4 | 0.4 | 0.7 | 1.9 | 10.6 | 40.5 | 141.2 | 367.0 | 699.3 | 42.1
2012 | 45.7 | 0.5 | 0.3 | 0.3 | 0.3 | 0.7 | 1.8 | 10.2 | 39.4 | 140.0 | 364.0 | 687.8 | 41.5
2011 | 45.9 | 0.8 | 0.3 | 0.3 | 0.4 | 0.6 | 1.8 | 10.4 | 39.5 | 144.3 | 374.9 | 697.9 | 42.5
2010 | 44.7 | 0.9 | 0.3 | 0.3 | 0.3 | 0.7 | 1.7 | 9.9 | 39.0 | 146.3 | 369.9 | 690.7 | 42.2
2009 | 44.8 | 0.7 | 0.4 | 0.3 | 0.4 | 0.7 | 1.8 | 10.4 | 40.0 | 147.5 | 376.4 | 684.9 | 42.7
2008 | 46.4 | 0.8 | 0.3 | 0.3 | 0.4 | 0.6 | 1.9 | 9.9 | 41.1 | 155.9 | 395.4 | 722.7 | 44.7
2007 | 42.5 | 1.0 | 0.4 | 0.3 | 0.3 | 0.7 | 1.9 | 9.5 | 38.6 | 145.5 | 367.1 | 652.0 | 41.4
2006 | 41.8 | 0.7 | 0.3 | 0.3 | 0.4 | 0.6 | 1.9 | 9.1 | 38.8 | 147.0 | 362.0 | 641.3 | 41.0
2005 | 44.3 | 0.8 | 0.4 | 0.3 | 0.3 | 0.7 | 2.0 | 9.4 | 41.6 | 158.4 | 385.0 | 691.9 | 43.9
2004 | 41.7 | 0.9 | 0.3 | 0.3 | 0.4 | 0.6 | 2.0 | 8.4 | 40.1 | 152.1 | 366.2 | 643.2 | 41.6
2003 | 43.6 | 0.8 | 0.4 | 0.3 | 0.5 | 0.7 | 2.2 | 8.7 | 43.1 | 161.7 | 382.2 | 670.2 | 43.7
2002 | 43.4 | 1.0 | 0.4 | 0.3 | 0.5 | 0.8 | 2.3 | 8.7 | 42.2 | 162.0 | 385.8 | 670.3 | 43.9
2001 | 43.2 | 1.0 | 0.3 | 0.3 | 0.4 | 0.7 | 2.2 | 8.4 | 44.5 | 167.3 | 379.3 | 658.3 | 43.9
2000 | 43.4 | 0.9 | 0.3 | 0.3 | 0.5 | 0.7 | 2.1 | 8.6 | 44.2 | 169.4 | 386.1 | 648.6 | 44.2
1999 | 44.5 | 0.9 | 0.4 | 0.3 | 0.5 | 0.8 | 2.0 | 8.5 | 47.5 | 177.2 | 397.8 | 646.0 | 45.4
Alzheimer disease (G30)
2022 | 36.0 | * | * | * | * | * | * | 0.3 | 3.5 | 26.7 | 206.2 | 1,131.5 | 28.9
2021 | 36.0 | * | * | * | * | * | * | 0.3 | 3.2 | 26.4 | 214.3 | 1,243.6 | 31.0
2020 | 40.7 | * | * | * | * | * | * | 0.2 | 3.3 | 28.6 | 229.3 | 1,287.3 | 32.4
2019 | 37.0 | * | * | * | * | * | * | 0.3 | 3.0 | 24.9 | 210.2 | 1,191.3 | 29.8
2018 | 37.3 | * | * | * | * | * | * | 0.3 | 2.9 | 24.7 | 213.9 | 1,225.3 | 30.5
2017 | 37.3 | * | * | * | * | * | * | 0.2 | 2.8 | 24.5 | 219.7 | 1,244.7 | 31.0
2016 | 35.9 | * | * | * | * | * | * | 0.2 | 2.7 | 23.6 | 214.1 | 1,216.9 | 30.3
2015 | 34.4 | * | * | * | * | * | * | 0.2 | 2.4 | 22.4 | 211.9 | 1,174.2 | 29.4
2014 | 29.3 | * | * | * | * | * | * | 0.2 | 2.1 | 19.6 | 185.6 | 1,006.8 | 25.4
2013 | 26.8 | * | * | * | * | * | * | 0.2 | 2.2 | 18.1 | 171.6 | 929.5 | 23.5
2012 | 26.6 | * | * | * | * | * | * | 0.2 | 2.2 | 17.9 | 175.4 | 936.1 | 23.8
2011 | 27.3 | * | * | * | * | * | * | 0.2 | 2.2 | 19.2 | 183.9 | 967.1 | 24.7
2010 | 27.0 | * | * | * | * | * | * | 0.3 | 2.1 | 19.8 | 184.5 | 987.1 | 25.1
2009 | 25.8 | * | * | * | * | * | * | 0.2 | 2.0 | 19.4 | 179.1 | 945.3 | 24.2
2008 | 27.1 | * | * | * | * | * | * | 0.2 | 2.2 | 21.1 | 192.5 | 1,002.2 | 25.8
2007 | 24.8 | * | * | * | * | * | * | 0.2 | 2.2 | 20.2 | 175.8 | 928.7 | 23.8
2006 | 24.3 | * | * | * | * | * | * | 0.2 | 2.1 | 19.9 | 175.0 | 923.4 | 23.7
2005 | 24.2 | * | * | * | * | * | * | 0.2 | 2.1 | 20.2 | 177.0 | 935.5 | 24.0
2004 | 22.5 | * | * | * | * | * | * | 0.2 | 1.8 | 19.5 | 168.5 | 875.3 | 22.6
2003 | 21.9 | * | * | * | * | * | * | 0.2 | 2.0 | 20.7 | 164.1 | 846.8 | 22.1
2002 | 20.5 | * | * | * | * | * | * | 0.1 | 1.9 | 19.6 | 157.7 | 790.9 | 20.8
2001 | 18.9 | * | * | * | * | * | * | 0.2 | 2.1 | 18.6 | 147.2 | 725.4 | 19.3
2000 | 17.6 | * | * | * | * | * | * | 0.2 | 2.0 | 18.7 | 139.6 | 667.7 | 18.1
1999 | 16.0 | * | * | * | * | * | * | 0.2 | 1.9 | 17.4 | 129.5 | 601.3 | 16.5
Diabetes mellitus (E10–E14)
2022 | 30.4 | * | * | 0.1 | 0.7 | 2.6 | 6.6 | 18.2 | 41.4 | 79.8 | 150.6 | 287.3 | 24.1
2021 | 31.1 | * | * | 0.1 | 0.8 | 2.8 | 6.8 | 18.7 | 43.5 | 83.0 | 160.4 | 309.9 | 25.4
2020 | 31.0 | * | * | 0.1 | 0.7 | 2.5 | 6.9 | 18.7 | 42.5 | 83.6 | 154.7 | 293.4 | 24.8
2019 | 26.7 | * | * | 0.1 | 0.6 | 1.9 | 5.3 | 15.5 | 36.5 | 73.3 | 138.9 | 259.5 | 21.6
2018 | 26.0 | * | * | 0.1 | 0.6 | 1.8 | 5.5 | 15.4 | 35.3 | 72.1 | 137.5 | 260.4 | 21.4
2017 | 25.7 | * | * | 0.1 | 0.6 | 1.8 | 5.2 | 15.1 | 35.5 | 71.9 | 140.8 | 262.4 | 21.5
2016 | 24.8 | * | * | 0.1 | 0.5 | 1.8 | 5.1 | 14.6 | 34.4 | 69.9 | 137.9 | 263.6 | 21.0
2015 | 24.7 | * | * | 0.1 | 0.4 | 1.8 | 4.9 | 14.4 | 34.7 | 70.6 | 143.0 | 267.0 | 21.3
2014 | 24.0 | * | * | 0.1 | 0.4 | 1.6 | 4.9 | 13.9 | 33.3 | 69.0 | 141.8 | 268.6 | 20.9
2013 | 23.9 | * | * | 0.1 | 0.4 | 1.6 | 4.8 | 13.5 | 33.2 | 68.5 | 145.7 | 279.5 | 21.2
2012 | 23.6 | * | * | 0.1 | 0.4 | 1.5 | 4.6 | 13.0 | 32.5 | 69.7 | 145.8 | 285.7 | 21.2
2011 | 23.7 | * | * | 0.1 | 0.4 | 1.6 | 4.5 | 13.4 | 33.3 | 72.0 | 148.8 | 289.5 | 21.6
2010 | 22.4 | * | * | 0.1 | 0.4 | 1.5 | 4.4 | 12.5 | 32.0 | 67.6 | 144.1 | 285.5 | 20.8
2009 | 22.4 | * | * | 0.1 | 0.4 | 1.5 | 4.5 | 12.8 | 32.1 | 69.6 | 145.8 | 282.6 | 21.0
2008 | 23.2 | * | * | 0.1 | 0.5 | 1.4 | 4.4 | 12.6 | 33.3 | 74.7 | 153.2 | 298.9 | 22.0
2007 | 23.7 | * | * | 0.1 | 0.4 | 1.5 | 4.6 | 13.1 | 34.1 | 76.7 | 161.9 | 302.2 | 22.8
2006 | 24.3 | * | * | 0.1 | 0.4 | 1.7 | 4.8 | 13.1 | 35.8 | 80.6 | 166.2 | 310.4 | 23.6
2005 | 25.4 | * | * | 0.1 | 0.5 | 1.6 | 4.7 | 13.4 | 36.9 | 85.7 | 177.0 | 338.8 | 24.9
2004 | 25.0 | * | * | 0.1 | 0.4 | 1.5 | 4.6 | 13.4 | 36.8 | 86.2 | 176.6 | 328.2 | 24.7
2003 | 25.6 | * | * | 0.1 | 0.4 | 1.7 | 4.6 | 13.9 | 38.3 | 90.0 | 180.7 | 335.1 | 25.5
2002 | 25.5 | * | * | 0.1 | 0.4 | 1.6 | 4.8 | 13.7 | 37.5 | 90.9 | 182.4 | 337.0 | 25.6
2001 | 25.0 | * | * | 0.1 | 0.4 | 1.5 | 4.3 | 13.6 | 38.1 | 91.0 | 181.1 | 328.6 | 25.4
2000 | 24.6 | * | * | 0.1 | 0.4 | 1.6 | 4.3 | 13.1 | 37.8 | 90.7 | 179.5 | 319.7 | 25.0
1999 | 24.5 | * | * | 0.1 | 0.4 | 1.4 | 4.3 | 12.9 | 38.3 | 91.8 | 178.0 | 317.2 | 25.0
Nephritis, nephrotic syndrome and nephrosis (N00–N07,N17–N19,N25–N27)
2022 | 17.4 | 1.0 | * | * | 0.1 | 0.8 | 2.4 | 6.6 | 15.8 | 38.3 | 97.0 | 264.2 | 13.8
2021 | 16.4 | 1.3 | * | * | 0.1 | 0.8 | 2.2 | 6.2 | 14.9 | 36.4 | 96.1 | 271.1 | 13.6
2020 | 15.9 | 1.2 | * | * | 0.2 | 0.7 | 2.0 | 5.8 | 14.7 | 35.2 | 89.3 | 248.1 | 12.7
2019 | 15.7 | 1.6 | * | * | 0.2 | 0.7 | 1.8 | 5.6 | 13.8 | 34.7 | 92.2 | 250.9 | 12.7
2018 | 15.7 | 2.0 | * | * | 0.1 | 0.6 | 1.8 | 5.4 | 13.6 | 35.6 | 94.3 | 257.9 | 12.9
2017 | 15.5 | 2.0 | * | * | 0.1 | 0.6 | 1.7 | 5.2 | 13.5 | 34.7 | 95.8 | 267.1 | 13.0
2016 | 15.5 | 1.6 | * | * | 0.1 | 0.6 | 1.8 | 5.0 | 13.6 | 34.6 | 98.1 | 270.1 | 13.1
2015 | 15.5 | 2.1 | * | * | 0.1 | 0.6 | 1.7 | 4.9 | 13.3 | 35.1 | 99.7 | 281.8 | 13.4
2014 | 15.1 | 2.3 | * | * | 0.2 | 0.5 | 1.7 | 4.7 | 12.6 | 34.3 | 98.6 | 282.4 | 13.2
2013 | 14.9 | 2.2 | * | * | 0.1 | 0.6 | 1.5 | 4.6 | 12.6 | 33.8 | 99.0 | 285.4 | 13.2
2012 | 14.5 | 2.1 | * | * | 0.2 | 0.5 | 1.6 | 4.7 | 12.3 | 33.3 | 99.9 | 280.0 | 13.1
2011 | 14.6 | 1.9 | * | * | 0.2 | 0.5 | 1.6 | 4.4 | 12.5 | 34.2 | 101.4 | 292.1 | 13.4
2010 | 16.3 | 2.7 | * | 0.1 | 0.2 | 0.6 | 1.8 | 4.9 | 13.9 | 39.3 | 115.7 | 333.8 | 15.3
2009 | 16.0 | 2.8 | * | * | 0.2 | 0.7 | 2.0 | 5.2 | 13.5 | 38.7 | 115.1 | 321.4 | 15.1
2008 | 15.9 | 3.5 | * | * | 0.2 | 0.6 | 1.8 | 5.0 | 14.1 | 39.9 | 113.3 | 325.6 | 15.1
2007 | 15.4 | 3.5 | 0.1 | 0.1 | 0.2 | 0.7 | 1.8 | 5.1 | 13.4 | 39.4 | 112.4 | 317.9 | 14.9
2006 | 15.2 | 4.0 | * | * | 0.2 | 0.7 | 1.8 | 5.2 | 13.7 | 38.8 | 111.0 | 316.2 | 14.8
2005 | 14.9 | 4.0 | * | 0.1 | 0.2 | 0.7 | 1.7 | 4.8 | 13.5 | 38.8 | 110.2 | 313.1 | 14.7
2004 | 14.5 | 4.3 | * | 0.1 | 0.2 | 0.6 | 1.8 | 5.0 | 13.5 | 38.1 | 108.2 | 306.4 | 14.5
2003 | 14.6 | 4.6 | * | 0.1 | 0.2 | 0.7 | 1.8 | 4.9 | 13.6 | 39.7 | 109.3 | 309.3 | 14.7
2002 | 14.2 | 4.4 | * | 0.1 | 0.2 | 0.7 | 1.7 | 4.7 | 12.9 | 39.0 | 108.9 | 303.4 | 14.4
2001 | 13.9 | 3.3 | * | * | 0.2 | 0.6 | 1.7 | 4.6 | 13.1 | 40.0 | 104.0 | 293.8 | 14.1
2000 | 13.2 | 4.3 | * | 0.1 | 0.2 | 0.6 | 1.6 | 4.4 | 12.8 | 38.0 | 100.8 | 277.8 | 13.5
1999 | 12.7 | 4.4 | * | 0.1 | 0.2 | 0.6 | 1.6 | 4.0 | 12.0 | 37.1 | 97.6 | 268.9 | 13.0
Chronic liver disease and cirrhosis (K70,K73–K74)
2022 | 16.4 | * | * | * | 0.1 | 3.9 | 12.6 | 23.3 | 39.2 | 39.0 | 36.7 | 30.2 | 13.8
2021 | 17.0 | * | * | * | 0.1 | 4.0 | 13.4 | 25.8 | 41.3 | 38.4 | 36.4 | 31.0 | 14.5
2020 | 15.7 | * | * | * | 0.1 | 3.5 | 11.7 | 23.5 | 38.1 | 36.5 | 34.5 | 27.0 | 13.3
2019 | 13.5 | * | * | * | 0.1 | 2.4 | 8.2 | 19.8 | 33.9 | 33.1 | 32.2 | 26.5 | 11.3
2018 | 13.1 | * | * | * | 0.1 | 2.2 | 7.5 | 19.6 | 33.0 | 32.5 | 32.5 | 25.5 | 11.1
2017 | 12.8 | * | * | * | 0.1 | 2.0 | 7.3 | 19.6 | 32.7 | 31.7 | 31.3 | 26.8 | 10.9
2016 | 12.5 | * | * | * | 0.1 | 2.1 | 7.0 | 19.5 | 32.4 | 30.7 | 31.9 | 24.5 | 10.7
2015 | 12.5 | * | * | * | 0.1 | 1.9 | 7.0 | 20.5 | 32.5 | 30.5 | 31.9 | 25.1 | 10.8
2014 | 12.0 | * | * | * | 0.1 | 1.7 | 6.4 | 19.9 | 31.9 | 29.6 | 30.4 | 23.4 | 10.4
2013 | 11.5 | * | * | * | 0.1 | 1.6 | 6.2 | 20.1 | 30.4 | 28.1 | 29.9 | 23.0 | 10.2
2012 | 11.1 | * | * | * | 0.1 | 1.4 | 6.1 | 20.1 | 29.1 | 27.6 | 29.3 | 21.4 | 9.9
2011 | 10.8 | * | * | * | 0.1 | 1.2 | 6.0 | 19.8 | 28.2 | 26.3 | 29.3 | 22.1 | 9.7
2010 | 10.3 | * | * | * | 0.1 | 1.2 | 5.9 | 19.2 | 26.8 | 26.3 | 27.7 | 21.8 | 9.4
2009 | 10.0 | * | * | * | 0.1 | 1.1 | 6.0 | 18.7 | 25.9 | 25.4 | 27.2 | 21.1 | 9.1
2008 | 9.9 | * | * | * | 0.1 | 1.1 | 6.1 | 18.5 | 25.0 | 26.3 | 28.0 | 21.9 | 9.2
2007 | 9.7 | * | * | * | 0.1 | 1.0 | 6.0 | 18.7 | 24.2 | 26.2 | 28.2 | 21.7 | 9.1
2006 | 9.2 | * | * | * | 0.1 | 0.8 | 5.9 | 17.8 | 22.6 | 25.6 | 28.9 | 21.1 | 8.8
2005 | 9.3 | * | * | * | 0.1 | 0.8 | 6.2 | 17.7 | 23.3 | 26.8 | 28.9 | 21.3 | 8.9
2004 | 9.2 | * | * | * | * | 0.8 | 6.4 | 18.0 | 22.4 | 27.4 | 28.7 | 21.1 | 9.0
2003 | 9.5 | * | * | * | * | 0.9 | 6.8 | 18.3 | 22.9 | 29.2 | 29.9 | 21.2 | 9.3
2002 | 9.5 | * | * | * | 0.1 | 1.0 | 7.1 | 18.0 | 22.8 | 29.3 | 31.3 | 22.5 | 9.4
2001 | 9.5 | * | * | * | 0.1 | 1.0 | 7.4 | 18.4 | 22.9 | 29.8 | 30.2 | 22.7 | 9.5
2000 | 9.4 | * | * | * | 0.1 | 1.0 | 7.5 | 17.7 | 23.8 | 29.8 | 31.0 | 23.1 | 9.5
1999 | 9.4 | * | * | * | 0.1 | 1.0 | 7.3 | 17.4 | 23.7 | 30.6 | 31.9 | 23.2 | 9.6
Intentional self-harm (suicide) (*U03,X60–X84,Y87.0)
2022 | 14.8 | … | … | 1.2 | 13.6 | 19.0 | 18.7 | 19.2 | 18.7 | 16.0 | 20.3 | 23.0 | 14.2
2021 | 14.5 | … | … | 1.5 | 15.2 | 19.5 | 18.1 | 18.2 | 17.0 | 15.3 | 19.6 | 22.4 | 14.1
2020 | 14.0 | … | … | 1.5 | 14.2 | 18.4 | 17.4 | 18.0 | 16.9 | 14.5 | 18.4 | 20.9 | 13.5
2019 | 14.5 | … | … | 1.3 | 13.9 | 17.5 | 18.1 | 19.6 | 19.4 | 15.5 | 18.6 | 20.1 | 13.9
2018 | 14.8 | … | … | 1.5 | 14.5 | 17.6 | 18.2 | 20.0 | 20.2 | 16.3 | 18.7 | 19.1 | 14.2
2017 | 14.5 | … | … | 1.3 | 14.5 | 17.5 | 17.9 | 20.2 | 19.0 | 15.6 | 18.0 | 20.1 | 14.0
2016 | 13.9 | … | … | 1.1 | 13.2 | 16.5 | 17.4 | 19.7 | 18.7 | 15.4 | 18.2 | 19.0 | 13.5
2015 | 13.7 | … | … | 1.0 | 12.5 | 15.7 | 17.1 | 20.3 | 18.9 | 15.2 | 17.9 | 19.4 | 13.3
2014 | 13.4 | … | … | 1.0 | 11.6 | 15.1 | 16.6 | 20.2 | 18.8 | 15.6 | 17.5 | 19.3 | 13.0
2013 | 13.0 | … | … | 1.0 | 11.1 | 14.8 | 16.2 | 19.7 | 18.1 | 15.0 | 17.1 | 18.6 | 12.6
2012 | 12.9 | … | … | 0.8 | 11.1 | 14.7 | 16.7 | 20.0 | 18.0 | 14.0 | 16.8 | 17.8 | 12.6
2011 | 12.7 | … | … | 0.7 | 11.0 | 14.6 | 16.2 | 19.8 | 17.1 | 14.1 | 16.5 | 16.9 | 12.3
2010 | 12.4 | … | … | 0.7 | 10.5 | 14.0 | 16.0 | 19.6 | 17.5 | 13.7 | 15.7 | 17.6 | 12.1
2009 | 12.0 | … | … | 0.6 | 10.0 | 13.1 | 16.1 | 19.2 | 16.4 | 13.7 | 15.8 | 16.4 | 11.8
2008 | 11.8 | … | … | 0.5 | 9.9 | 13.2 | 15.9 | 18.6 | 16.0 | 13.6 | 16.1 | 16.4 | 11.6
2007 | 11.5 | … | … | 0.5 | 9.6 | 13.3 | 15.7 | 17.7 | 15.3 | 12.4 | 16.2 | 17.0 | 11.3
2006 | 11.2 | … | … | 0.5 | 9.8 | 12.7 | 15.2 | 17.2 | 14.4 | 12.4 | 15.8 | 17.3 | 11.0
2005 | 11.0 | … | … | 0.7 | 9.9 | 12.7 | 15.1 | 16.5 | 13.7 | 12.4 | 16.8 | 18.3 | 10.9
2004 | 11.1 | … | … | 0.7 | 10.3 | 12.9 | 15.2 | 16.6 | 13.7 | 12.2 | 16.3 | 17.6 | 11.0
2003 | 10.9 | … | … | 0.6 | 9.6 | 12.9 | 15.0 | 15.9 | 13.7 | 12.6 | 16.4 | 17.9 | 10.8
2002 | 11.0 | … | … | 0.6 | 9.8 | 12.8 | 15.3 | 15.8 | 13.5 | 13.4 | 17.7 | 18.9 | 10.9
2001 | 10.7 | … | … | 0.7 | 9.9 | 12.8 | 14.7 | 15.1 | 13.2 | 13.2 | 17.4 | 17.8 | 10.7
2000 | 10.4 | … | … | 0.7 | 10.2 | 12.0 | 14.5 | 14.4 | 12.1 | 12.5 | 17.6 | 19.6 | 10.4
1999 | 10.5 | … | … | 0.6 | 10.1 | 12.7 | 14.3 | 13.9 | 12.2 | 13.4 | 18.1 | 19.3 | 10.5
Influenza and pneumonia (J09–J18)
2022 | 14.1 | 4.2 | 0.9 | 0.3 | 0.4 | 1.1 | 2.3 | 4.7 | 12.0 | 27.8 | 72.9 | 244.2 | 11.3
2021 | 12.6 | 3.5 | 0.3 | 0.1 | 0.3 | 0.9 | 1.9 | 4.4 | 11.3 | 25.3 | 69.9 | 231.8 | 10.5
2020 | 16.3 | 3.3 | 0.5 | 0.3 | 0.4 | 1.3 | 2.7 | 6.2 | 14.8 | 32.1 | 84.1 | 273.6 | 13.0
2019 | 15.2 | 4.1 | 0.8 | 0.3 | 0.4 | 1.0 | 2.3 | 5.1 | 12.5 | 27.3 | 77.2 | 294.7 | 12.3
2018 | 18.1 | 4.6 | 0.8 | 0.3 | 0.5 | 1.0 | 2.3 | 5.6 | 13.9 | 31.7 | 94.2 | 377.6 | 14.9
2017 | 17.1 | 4.0 | 0.7 | 0.3 | 0.4 | 0.9 | 1.9 | 4.8 | 12.0 | 29.6 | 93.8 | 375.3 | 14.3
2016 | 15.9 | 4.2 | 0.6 | 0.2 | 0.4 | 1.0 | 2.2 | 5.0 | 12.1 | 28.5 | 88.5 | 340.3 | 13.5
2015 | 17.8 | 4.4 | 0.6 | 0.2 | 0.4 | 0.9 | 1.7 | 4.7 | 11.3 | 29.5 | 101.6 | 421.4 | 15.2
2014 | 17.3 | 4.7 | 0.7 | 0.2 | 0.5 | 1.3 | 2.8 | 6.3 | 13.4 | 29.8 | 96.4 | 385.9 | 15.1
2013 | 18.0 | 4.5 | 0.6 | 0.3 | 0.4 | 1.0 | 2.2 | 5.1 | 12.2 | 29.5 | 103.7 | 441.0 | 15.9
2012 | 16.1 | 4.0 | 0.6 | 0.2 | 0.3 | 0.8 | 1.7 | 4.1 | 10.2 | 26.1 | 98.2 | 408.4 | 14.4
2011 | 17.3 | 5.2 | 0.7 | 0.3 | 0.5 | 1.2 | 2.1 | 5.0 | 11.0 | 28.9 | 104.0 | 439.2 | 15.7
2010 | 16.2 | 4.9 | 0.6 | 0.2 | 0.4 | 0.9 | 1.9 | 4.3 | 9.9 | 27.9 | 102.4 | 426.2 | 15.1
2009 | 17.5 | 6.3 | 0.9 | 0.6 | 1.0 | 2.0 | 3.2 | 6.5 | 11.7 | 29.5 | 107.0 | 433.8 | 16.5
2008 | 18.5 | 5.5 | 0.9 | 0.2 | 0.5 | 0.9 | 2.1 | 5.1 | 10.9 | 30.5 | 118.6 | 512.3 | 17.6
2007 | 17.5 | 5.4 | 0.7 | 0.3 | 0.4 | 0.8 | 1.8 | 4.3 | 9.5 | 28.2 | 113.5 | 506.7 | 16.8
2006 | 18.9 | 6.5 | 0.8 | 0.2 | 0.4 | 0.9 | 1.9 | 4.6 | 9.9 | 31.6 | 127.3 | 547.0 | 18.4
2005 | 21.3 | 6.6 | 0.7 | 0.3 | 0.4 | 0.9 | 2.1 | 5.1 | 11.2 | 35.1 | 142.0 | 644.9 | 21.0
2004 | 20.4 | 6.8 | 0.8 | 0.2 | 0.4 | 0.8 | 2.0 | 4.6 | 10.8 | 34.2 | 139.1 | 622.8 | 20.4
2003 | 22.5 | 8.1 | 1.0 | 0.4 | 0.5 | 1.0 | 2.2 | 5.2 | 11.2 | 36.9 | 150.8 | 703.0 | 22.6
2002 | 22.8 | 6.7 | 0.7 | 0.2 | 0.4 | 0.9 | 2.2 | 4.8 | 11.2 | 37.2 | 156.6 | 732.4 | 23.2
2001 | 21.8 | 7.5 | 0.7 | 0.2 | 0.5 | 0.9 | 2.2 | 4.6 | 10.8 | 36.2 | 148.3 | 700.1 | 22.2
2000 | 23.2 | 7.6 | 0.7 | 0.2 | 0.5 | 0.9 | 2.4 | 4.7 | 11.9 | 39.1 | 160.3 | 744.1 | 23.7
1999 | 22.8 | 8.4 | 0.8 | 0.2 | 0.5 | 0.8 | 2.4 | 4.6 | 11.0 | 37.2 | 157.0 | 751.8 | 23.5
Essential hypertension and hypertensive renal disease (I10,I12,I15)
2022 | 13.0 | * | * | * | 0.1 | 0.4 | 1.6 | 4.5 | 11.8 | 24.6 | 61.6 | 254.0 | 10.3
2021 | 12.9 | * | * | * | 0.1 | 0.4 | 1.5 | 4.8 | 12.1 | 24.9 | 63.2 | 270.8 | 10.7
2020 | 12.7 | * | * | * | 0.1 | 0.3 | 1.4 | 4.5 | 11.8 | 23.9 | 60.3 | 250.3 | 10.1
2019 | 11.1 | * | * | * | * | 0.3 | 1.2 | 3.6 | 9.8 | 20.9 | 54.3 | 227.1 | 8.9
2018 | 11.0 | * | * | * | * | 0.3 | 1.2 | 3.7 | 9.7 | 20.2 | 54.4 | 229.4 | 8.9
2017 | 10.8 | * | * | * | * | 0.3 | 1.3 | 3.9 | 9.5 | 19.7 | 55.8 | 231.4 | 9.0
2016 | 10.3 | * | * | * | * | 0.3 | 1.1 | 3.8 | 9.0 | 19.0 | 53.7 | 222.3 | 8.6
2015 | 10.0 | * | * | * | * | 0.3 | 1.2 | 3.4 | 8.8 | 18.1 | 54.1 | 222.7 | 8.5
2014 | 9.5 | * | * | * | 0.0 | 0.2 | 1.1 | 3.3 | 8.4 | 16.9 | 51.3 | 217.0 | 8.2
2013 | 9.7 | * | * | * | 0.1 | 0.3 | 1.0 | 3.5 | 8.0 | 17.3 | 53.7 | 231.6 | 8.5
2012 | 9.3 | * | * | * | * | 0.2 | 0.8 | 3.0 | 7.8 | 16.1 | 51.7 | 230.7 | 8.2
2011 | 8.9 | * | * | * | * | 0.2 | 1.0 | 3.1 | 7.0 | 16.6 | 51.4 | 222.7 | 8.1
2010 | 8.6 | * | * | * | 0.0 | 0.3 | 1.0 | 3.1 | 7.3 | 16.7 | 51.8 | 212.0 | 8.0
2009 | 8.4 | * | * | * | 0.1 | 0.3 | 1.0 | 3.1 | 7.1 | 16.3 | 51.0 | 208.0 | 7.8
2008 | 8.5 | * | * | * | 0.1 | 0.3 | 1.0 | 3.0 | 7.2 | 16.5 | 51.9 | 215.3 | 8.0
2007 | 8.0 | * | * | * | 0.1 | 0.2 | 0.9 | 2.8 | 6.4 | 15.9 | 49.2 | 209.1 | 7.6
2006 | 8.0 | * | * | * | 0.0 | 0.3 | 0.9 | 3.0 | 6.8 | 16.5 | 50.8 | 206.1 | 7.7
2005 | 8.4 | * | * | * | 0.1 | 0.2 | 0.9 | 2.7 | 6.4 | 17.5 | 55.5 | 228.0 | 8.3
2004 | 7.9 | * | * | * | 0.1 | 0.3 | 0.8 | 2.7 | 6.3 | 16.9 | 52.5 | 212.2 | 7.9
2003 | 7.6 | * | * | * | 0.1 | 0.2 | 0.8 | 2.5 | 6.3 | 16.8 | 51.6 | 199.4 | 7.6
2002 | 7.0 | * | * | * | 0.1 | 0.2 | 0.8 | 2.3 | 5.7 | 15.9 | 48.1 | 189.6 | 7.1
2001 | 6.8 | * | * | * | 0.1 | 0.3 | 0.7 | 2.4 | 5.8 | 15.4 | 47.6 | 175.6 | 6.9
2000 | 6.4 | * | * | * | * | 0.2 | 0.8 | 2.3 | 5.9 | 15.1 | 45.5 | 162.9 | 6.5
1999 | 6.1 | * | * | * | * | 0.2 | 0.7 | 2.2 | 5.5 | 15.2 | 43.6 | 152.1 | 6.2
Septicemia (A40–A41)
2022 | 12.7 | 3.3 | 0.4 | 0.1 | 0.3 | 1.0 | 2.3 | 6.2 | 14.7 | 31.4 | 66.9 | 145.4 | 10.1
2021 | 12.4 | 3.2 | 0.2 | 0.1 | 0.2 | 0.9 | 2.6 | 6.0 | 15.1 | 31.1 | 67.4 | 153.3 | 10.2
2020 | 12.2 | 3.1 | 0.3 | 0.1 | 0.2 | 0.8 | 2.3 | 6.2 | 14.7 | 29.7 | 63.5 | 143.1 | 9.7
2019 | 11.7 | 3.5 | 0.3 | 0.2 | 0.3 | 0.8 | 1.9 | 5.3 | 13.4 | 28.0 | 64.5 | 150.2 | 9.5
2018 | 12.4 | 3.9 | 0.3 | 0.1 | 0.2 | 0.9 | 2.0 | 5.7 | 14.1 | 30.0 | 69.4 | 167.4 | 10.2
2017 | 12.6 | 3.7 | 0.3 | 0.1 | 0.3 | 0.9 | 2.1 | 5.8 | 13.9 | 30.9 | 72.4 | 173.3 | 10.6
2016 | 12.6 | 4.8 | 0.4 | 0.2 | 0.3 | 0.9 | 2.2 | 5.8 | 14.3 | 30.6 | 73.9 | 174.2 | 10.7
2015 | 12.7 | 4.5 | 0.3 | 0.2 | 0.3 | 0.9 | 2.0 | 5.9 | 14.1 | 31.4 | 75.3 | 185.8 | 11.0
2014 | 12.2 | 4.0 | 0.3 | 0.2 | 0.3 | 0.8 | 2.1 | 5.8 | 14.2 | 31.1 | 73.1 | 176.9 | 10.7
2013 | 12.1 | 3.9 | 0.3 | 0.1 | 0.3 | 0.8 | 2.0 | 5.6 | 13.6 | 30.5 | 76.4 | 179.6 | 10.7
2012 | 11.4 | 4.5 | 0.4 | 0.1 | 0.3 | 0.8 | 1.9 | 5.3 | 12.9 | 29.2 | 73.9 | 173.4 | 10.3
2011 | 11.5 | 4.5 | 0.4 | 0.2 | 0.3 | 0.8 | 2.0 | 5.5 | 13.0 | 29.5 | 74.4 | 179.7 | 10.5
2010 | 11.3 | 5.5 | 0.4 | 0.2 | 0.3 | 0.8 | 1.9 | 5.2 | 12.6 | 30.1 | 76.0 | 179.0 | 10.6
2009 | 11.6 | 5.5 | 0.4 | 0.2 | 0.3 | 0.9 | 2.2 | 5.4 | 13.1 | 31.4 | 79.2 | 182.4 | 11.0
2008 | 11.8 | 7.0 | 0.6 | 0.2 | 0.3 | 0.9 | 2.1 | 5.7 | 13.3 | 31.4 | 82.0 | 189.8 | 11.3
2007 | 11.6 | 6.8 | 0.5 | 0.2 | 0.4 | 0.7 | 2.1 | 5.5 | 12.8 | 32.2 | 79.5 | 190.8 | 11.2
2006 | 11.5 | 6.7 | 0.6 | 0.2 | 0.3 | 0.7 | 2.0 | 5.2 | 12.6 | 31.6 | 82.1 | 193.0 | 11.2
2005 | 11.6 | 7.5 | 0.5 | 0.2 | 0.3 | 0.8 | 1.9 | 5.2 | 12.8 | 32.2 | 81.3 | 203.4 | 11.4
2004 | 11.4 | 6.8 | 0.5 | 0.2 | 0.3 | 0.8 | 1.9 | 5.4 | 12.8 | 32.1 | 81.5 | 199.6 | 11.3
2003 | 11.7 | 7.0 | 0.5 | 0.2 | 0.4 | 0.8 | 2.1 | 5.3 | 13.0 | 32.3 | 84.8 | 213.7 | 11.8
2002 | 11.8 | 7.5 | 0.5 | 0.2 | 0.3 | 0.8 | 1.9 | 5.2 | 12.6 | 34.5 | 86.3 | 213.4 | 11.9
2001 | 11.3 | 7.8 | 0.7 | 0.2 | 0.3 | 0.7 | 1.8 | 5.0 | 12.4 | 32.6 | 82.2 | 210.3 | 11.5
2000 | 11.1 | 7.2 | 0.6 | 0.2 | 0.3 | 0.7 | 1.9 | 4.9 | 11.9 | 31.0 | 80.4 | 215.7 | 11.3
1999 | 11.0 | 7.5 | 0.6 | 0.2 | 0.3 | 0.7 | 1.8 | 4.6 | 11.4 | 31.2 | 79.4 | 220.7 | 11.3
Parkinson disease (G20–G21)
2022 | 12.0 | * | * | * | * | * | * | 0.2 | 2.1 | 19.0 | 102.1 | 225.4 | 9.5
2021 | 11.6 | * | * | * | * | * | * | 0.2 | 2.0 | 18.6 | 102.5 | 246.0 | 9.8
2020 | 12.2 | * | * | * | * | * | * | 0.2 | 2.1 | 19.0 | 105.3 | 237.4 | 9.9
2019 | 10.8 | * | * | * | * | * | * | 0.2 | 1.9 | 16.8 | 93.3 | 215.9 | 8.8
2018 | 10.3 | * | * | * | * | * | * | 0.2 | 1.8 | 16.2 | 91.0 | 214.6 | 8.7
2017 | 9.8 | * | * | * | * | * | * | 0.1 | 1.7 | 15.7 | 89.6 | 206.3 | 8.4
2016 | 9.2 | * | * | * | * | * | * | 0.2 | 1.6 | 14.3 | 85.5 | 198.6 | 8.0
2015 | 8.7 | * | * | * | * | * | * | 0.2 | 1.5 | 13.8 | 82.4 | 190.6 | 7.7
2014 | 8.2 | * | * | * | * | * | * | 0.2 | 1.4 | 13.0 | 79.2 | 182.0 | 7.4
2013 | 8.0 | * | * | * | * | * | * | 0.2 | 1.5 | 12.7 | 78.5 | 178.2 | 7.3
2012 | 7.6 | * | * | * | * | * | * | 0.1 | 1.4 | 12.3 | 76.2 | 172.3 | 7.0
2011 | 7.4 | * | * | * | * | * | * | 0.1 | 1.3 | 12.8 | 76.0 | 168.1 | 7.0
2010 | 7.1 | * | * | * | * | * | * | 0.2 | 1.3 | 11.8 | 74.8 | 165.9 | 6.8
2009 | 6.7 | * | * | * | * | * | * | 0.2 | 1.3 | 11.2 | 70.8 | 157.0 | 6.5
2008 | 6.7 | * | * | * | * | * | * | 0.2 | 1.2 | 12.3 | 71.2 | 157.4 | 6.6
2007 | 6.7 | * | * | * | * | * | * | 0.1 | 1.2 | 11.7 | 71.5 | 157.0 | 6.5
2006 | 6.6 | * | * | * | * | * | * | 0.2 | 1.2 | 12.0 | 69.5 | 157.6 | 6.5
2005 | 6.6 | * | * | * | * | * | * | 0.2 | 1.4 | 12.8 | 71.1 | 156.0 | 6.6
2004 | 6.1 | * | * | * | * | * | * | 0.2 | 1.2 | 11.9 | 67.4 | 145.1 | 6.2
2003 | 6.2 | * | * | * | * | * | * | 0.2 | 1.3 | 12.6 | 67.6 | 145.8 | 6.3
2002 | 5.9 | * | * | * | * | * | * | 0.1 | 1.2 | 12.1 | 63.8 | 142.2 | 6.0
2001 | 5.8 | * | * | * | * | * | * | 0.1 | 1.2 | 11.7 | 64.5 | 137.0 | 5.9
2000 | 5.6 | * | * | * | * | * | * | 0.1 | 1.1 | 11.5 | 61.9 | 131.9 | 5.7
1999 | 5.2 | * | * | * | * | * | * | 0.1 | 1.0 | 11.0 | 58.2 | 124.4 | 5.4
Dementia-related causes^6^
2022 | 87.9 | * | * | 0.1 | * | * | 0.1 | 0.9 | 9.4 | 67.4 | 476.2 | 2,809.6 | 70.4
2021 | 84.3 | * | * | 0.1 | * | 0.0 | 0.2 | 0.9 | 8.6 | 65.0 | 477.6 | 2,949.3 | 72.4
2020 | 92.3 | * | * | * | * | 0.0 | 0.1 | 0.8 | 8.7 | 68.1 | 495.1 | 2,946.9 | 73.3
2019 | 82.8 | * | * | 0.1 | * | 0.1 | 0.1 | 0.9 | 8.2 | 59.3 | 448.6 | 2,688.9 | 66.6
2018 | 81.6 | * | * | * | * | 0.1 | 0.1 | 0.8 | 7.8 | 57.9 | 447.0 | 2,700.3 | 66.6
2017 | 80.4 | * | * | 0.0 | * | * | 0.1 | 0.7 | 7.5 | 56.9 | 450.9 | 2,707.3 | 66.7
2016 | 77.2 | * | * | 0.1 | * | 0.1 | 0.1 | 0.8 | 7.3 | 54.7 | 441.6 | 2,626.4 | 64.9
2015 | 76.5 | * | * | 0.1 | * | * | 0.1 | 0.8 | 6.8 | 53.0 | 447.2 | 2,637.4 | 65.2
2014 | 75.2 | * | 0.1 | 0.1 | * | * | 0.1 | 0.8 | 6.9 | 52.7 | 450.6 | 2,611.3 | 64.9
2013 | 74.1 | * | * | * | * | * | 0.1 | 0.9 | 7.4 | 52.2 | 449.7 | 2,601.8 | 64.8
2012 | 71.2 | * | 0.2 | * | * | * | 0.1 | 0.9 | 6.8 | 50.3 | 445.2 | 2,532.7 | 63.3
2011 | 68.3 | * | 0.1 | 0.1 | * | * | 0.1 | 0.8 | 6.5 | 50.4 | 436.6 | 2,458.6 | 61.8
2010 | 63.6 | * | * | * | * | * | 0.1 | 0.9 | 6.3 | 48.3 | 412.1 | 2,352.4 | 58.8
2009 | 57.9 | * | 0.1 | 0.1 | * | 0.1 | 0.2 | 0.8 | 5.7 | 45.2 | 383.3 | 2,151.3 | 54.2
2008 | 58.9 | * | 0.2 | 0.1 | * | * | 0.1 | 0.9 | 6.0 | 46.4 | 396.7 | 2,213.2 | 55.9
2007 | 51.8 | * | 0.2 | 0.1 | * | * | 0.1 | 0.8 | 5.5 | 42.3 | 350.0 | 1,976.0 | 49.8
2006 | 50.8 | * | 0.1 | 0.1 | * | * | 0.1 | 0.8 | 5.5 | 42.4 | 346.2 | 1,967.0 | 49.5
2005 | 43.8 | * | 0.2 | * | * | * | 0.1 | 0.6 | 4.5 | 36.3 | 302.1 | 1,735.4 | 43.4
2004 | 39.0 | * | 0.2 | 0.1 | * | * | 0.1 | 0.6 | 3.9 | 33.1 | 275.4 | 1,556.9 | 39.1
2003 | 38.1 | * | 0.2 | 0.1 | * | * | 0.1 | 0.6 | 4.0 | 34.1 | 269.5 | 1,523.1 | 38.4
2002 | 35.5 | * | 0.2 | 0.1 | * | * | 0.1 | 0.4 | 3.6 | 31.9 | 254.9 | 1,428.9 | 36.1
2001 | 32.5 | * | 0.2 | 0.0 | * | 0.1 | 0.1 | 0.5 | 3.8 | 30.5 | 234.6 | 1,299.3 | 33.1
2000 | 29.7 | * | 0.2 | 0.1 | 0.1 | 0.1 | 0.1 | 0.5 | 3.6 | 29.4 | 218.5 | 1,180.9 | 30.5
1999 | 26.7 | * | 0.2 | 0.1 | * | * | 0.1 | 0.4 | 3.4 | 27.0 | 197.9 | 1,062.5 | 27.5
Drug-induced causes^6^
2022 | 33.6 | 2.0 | 1.2 | 0.4 | 15.3 | 51.8 | 65.1 | 57.3 | 50.7 | 20.7 | 6.3 | 4.7 | 33.8
2021 | 33.5 | 2.1 | 0.8 | 0.3 | 17.5 | 54.2 | 64.0 | 56.2 | 48.0 | 18.5 | 6.0 | 5.3 | 33.6
2020 | 29.2 | 1.7 | 0.4 | 0.3 | 17.0 | 48.8 | 55.8 | 49.1 | 39.9 | 14.7 | 4.9 | 5.1 | 29.5
2019 | 22.7 | 1.3 | 0.3 | 0.2 | 11.5 | 36.9 | 42.3 | 38.9 | 32.7 | 12.6 | 5.2 | 4.6 | 22.8
2018 | 21.7 | 0.8 | 0.2 | 0.1 | 11.0 | 36.8 | 40.0 | 37.3 | 30.4 | 11.4 | 4.8 | 5.1 | 21.8
2017 | 22.7 | 0.9 | 0.2 | 0.2 | 13.0 | 39.8 | 40.6 | 39.8 | 30.0 | 10.5 | 4.5 | 5.3 | 22.8
2016 | 20.8 | 0.9 | 0.3 | 0.1 | 12.8 | 35.9 | 36.6 | 36.5 | 27.7 | 9.2 | 4.1 | 5.3 | 20.8
2015 | 17.2 | 0.7 | 0.4 | 0.1 | 10.0 | 28.0 | 29.6 | 31.9 | 23.3 | 8.1 | 4.4 | 5.6 | 17.2
2014 | 15.6 | 0.6 | 0.3 | 0.1 | 8.9 | 24.0 | 26.2 | 29.8 | 21.7 | 7.6 | 4.4 | 5.0 | 15.5
2013 | 14.7 | 0.8 | 0.3 | 0.1 | 8.6 | 21.7 | 24.1 | 29.0 | 20.6 | 7.1 | 4.4 | 5.3 | 14.6
2012 | 14.0 | 0.8 | 0.2 | 0.1 | 8.3 | 20.9 | 23.1 | 28.3 | 17.9 | 6.5 | 4.0 | 5.1 | 13.8
2011 | 14.0 | 0.6 | 0.2 | 0.1 | 8.9 | 20.9 | 23.4 | 28.2 | 17.1 | 6.0 | 4.0 | 4.9 | 13.9
2010 | 13.1 | 0.6 | 0.3 | 0.2 | 8.4 | 19.2 | 21.7 | 26.5 | 16.2 | 5.2 | 4.0 | 5.5 | 12.9
2009 | 12.8 | 0.8 | 0.2 | 0.1 | 8.0 | 17.8 | 21.5 | 26.9 | 14.9 | 5.4 | 4.5 | 5.1 | 12.6
2008 | 12.7 | 0.5 | 0.3 | 0.1 | 8.3 | 17.4 | 22.2 | 26.8 | 14.0 | 5.2 | 4.0 | 5.0 | 12.6
2007 | 12.7 | 0.8 | 0.3 | 0.2 | 8.5 | 17.5 | 22.6 | 26.8 | 13.4 | 4.6 | 3.9 | 5.2 | 12.6
2006 | 12.9 | 1.1 | 0.2 | 0.1 | 8.5 | 17.2 | 23.5 | 26.7 | 12.1 | 5.2 | 6.0 | 8.8 | 12.8
2005 | 11.3 | 0.9 | 0.2 | 0.1 | 7.3 | 14.6 | 21.5 | 23.6 | 10.6 | 4.7 | 5.4 | 8.3 | 11.3
2004 | 10.5 | 0.7 | 0.2 | 0.2 | 6.9 | 12.9 | 21.1 | 21.7 | 9.0 | 4.2 | 4.8 | 6.7 | 10.5
2003 | 9.9 | 0.6 | 0.2 | 0.1 | 6.3 | 12.3 | 20.7 | 20.0 | 8.0 | 4.1 | 4.2 | 6.3 | 9.9
2002 | 9.1 | 0.7 | 0.2 | 0.1 | 5.4 | 11.3 | 19.8 | 18.0 | 6.8 | 3.6 | 3.8 | 6.0 | 9.1
2001 | 7.6 | 0.5 | 0.2 | 0.1 | 4.5 | 9.5 | 17.0 | 14.7 | 5.4 | 3.0 | 3.5 | 5.2 | 7.6
2000 | 7.0 | * | * | 0.1 | 4.0 | 8.8 | 16.0 | 13.2 | 4.9 | 2.6 | 3.5 | 5.7 | 7.0
1999 | 6.9 | 0.6 | 0.2 | 0.1 | 3.5 | 8.9 | 15.7 | 12.6 | 4.9 | 3.0 | 3.8 | 4.8 | 6.8
Alcohol-induced causes^6^
2022 | 15.4 | * | * | * | 0.5 | 6.6 | 17.0 | 26.8 | 39.7 | 28.8 | 15.7 | 7.6 | 13.5
2021 | 16.3 | * | * | * | 0.5 | 6.7 | 18.0 | 30.3 | 42.0 | 29.6 | 15.4 | 7.8 | 14.4
2020 | 14.9 | * | * | * | 0.4 | 6.0 | 16.0 | 27.5 | 39.3 | 27.1 | 14.4 | 6.5 | 13.1
2019 | 11.9 | * | * | * | 0.4 | 4.2 | 11.1 | 22.0 | 32.5 | 22.5 | 12.6 | 6.4 | 10.4
2018 | 11.4 | * | * | * | 0.3 | 3.7 | 10.0 | 21.6 | 31.5 | 22.2 | 12.4 | 6.1 | 9.9
2017 | 11.0 | * | * | * | 0.3 | 3.4 | 9.4 | 21.8 | 30.2 | 20.9 | 11.7 | 6.4 | 9.6
2016 | 10.8 | * | * | * | 0.4 | 3.6 | 9.2 | 21.4 | 29.7 | 20.3 | 11.8 | 6.3 | 9.5
2015 | 10.3 | * | * | * | 0.4 | 3.2 | 8.7 | 21.6 | 28.2 | 19.1 | 11.2 | 5.8 | 9.1
2014 | 9.6 | * | * | * | 0.3 | 2.8 | 8.0 | 20.4 | 26.8 | 17.6 | 10.5 | 5.6 | 8.5
2013 | 9.2 | * | * | * | 0.3 | 2.5 | 7.7 | 20.1 | 25.3 | 16.6 | 10.3 | 4.9 | 8.2
2012 | 8.8 | * | * | * | 0.4 | 2.4 | 7.4 | 20.0 | 24.1 | 15.8 | 10.3 | 5.0 | 8.0
2011 | 8.6 | * | * | * | 0.4 | 2.1 | 7.6 | 19.8 | 22.7 | 15.2 | 9.6 | 5.1 | 7.7
2010 | 8.3 | * | * | * | 0.3 | 2.2 | 7.5 | 19.1 | 21.9 | 15.8 | 9.6 | 5.3 | 7.6
2009 | 8.0 | * | * | * | 0.4 | 1.8 | 7.6 | 18.7 | 20.8 | 15.1 | 9.2 | 4.8 | 7.4
2008 | 8.0 | * | * | * | 0.4 | 2.0 | 7.6 | 18.6 | 20.7 | 15.3 | 9.4 | 5.2 | 7.4
2007 | 7.7 | * | * | * | 0.4 | 1.9 | 7.3 | 18.2 | 19.9 | 15.2 | 9.6 | 5.0 | 7.2
2006 | 7.4 | * | * | * | 0.3 | 1.6 | 7.5 | 17.5 | 19.2 | 14.5 | 9.7 | 5.3 | 7.0
2005 | 7.3 | * | * | * | 0.4 | 1.4 | 7.5 | 17.6 | 19.4 | 14.9 | 9.2 | 5.0 | 7.0
2004 | 7.2 | * | * | * | 0.3 | 1.6 | 7.7 | 17.3 | 18.6 | 15.5 | 9.2 | 4.6 | 7.0
2003 | 7.1 | * | * | * | 0.3 | 1.5 | 8.1 | 17.3 | 18.5 | 15.0 | 9.2 | 4.3 | 7.0
2002 | 7.0 | * | * | * | 0.3 | 1.5 | 8.1 | 16.9 | 18.3 | 15.4 | 9.3 | 4.6 | 6.9
2001 | 7.1 | * | * | * | 0.3 | 1.6 | 8.3 | 17.1 | 18.3 | 15.5 | 9.6 | 5.1 | 7.0
2000 | 7.0 | * | * | * | 0.2 | 1.6 | 8.5 | 16.3 | 18.7 | 15.8 | 9.9 | 5.4 | 7.0
1999 | 7.0 | * | * | * | 0.3 | 1.6 | 8.5 | 16.4 | 18.7 | 15.9 | 10.6 | 5.5 | 7.1
Injury by firearms^6^
2022 | 14.5 | * | 0.9 | 1.5 | 21.1 | 22.9 | 18.1 | 14.8 | 13.4 | 11.9 | 16.5 | 18.5 | 14.2
2021 | 14.7 | * | 0.9 | 1.6 | 23.5 | 24.8 | 18.1 | 14.5 | 12.1 | 11.7 | 16.2 | 18.3 | 14.6
2020 | 13.7 | * | 0.8 | 1.5 | 22.2 | 22.7 | 16.7 | 13.3 | 11.8 | 10.9 | 15.3 | 16.2 | 13.6
2019 | 12.1 | * | 0.5 | 1.0 | 17.4 | 18.1 | 14.6 | 12.7 | 12.3 | 11.1 | 15.0 | 16.1 | 11.9
2018 | 12.1 | * | 0.6 | 1.1 | 17.2 | 17.7 | 14.6 | 12.8 | 12.7 | 12.0 | 15.4 | 14.7 | 11.9
2017 | 12.2 | * | 0.5 | 1.1 | 17.7 | 18.5 | 14.4 | 13.1 | 12.3 | 11.4 | 14.8 | 15.6 | 12.0
2016 | 12.0 | * | 0.6 | 0.9 | 17.2 | 18.2 | 14.5 | 12.8 | 11.9 | 11.4 | 14.7 | 14.3 | 11.8
2015 | 11.3 | * | 0.5 | 0.9 | 15.7 | 16.8 | 13.1 | 12.4 | 11.7 | 11.3 | 14.5 | 14.5 | 11.1
2014 | 10.5 | * | 0.4 | 0.9 | 14.0 | 14.7 | 12.1 | 12.2 | 11.4 | 11.5 | 13.9 | 15.0 | 10.3
2013 | 10.6 | * | 0.4 | 0.8 | 14.1 | 15.3 | 12.3 | 12.3 | 11.5 | 11.3 | 14.1 | 13.9 | 10.4
2012 | 10.7 | * | 0.4 | 0.8 | 14.7 | 15.3 | 12.4 | 12.4 | 11.6 | 10.8 | 14.1 | 13.6 | 10.5
2011 | 10.4 | * | 0.5 | 0.8 | 14.4 | 15.0 | 11.7 | 12.2 | 11.0 | 10.9 | 13.7 | 13.1 | 10.2
2010 | 10.3 | * | 0.4 | 0.7 | 14.2 | 15.0 | 11.7 | 12.0 | 11.1 | 10.7 | 12.7 | 13.2 | 10.1
2009 | 10.2 | * | 0.4 | 0.7 | 14.4 | 14.5 | 11.9 | 11.8 | 10.8 | 10.9 | 13.3 | 12.5 | 10.1
2008 | 10.4 | * | 0.5 | 0.7 | 15.4 | 15.4 | 11.8 | 11.5 | 10.8 | 10.7 | 13.2 | 12.5 | 10.3
2007 | 10.4 | * | 0.4 | 0.8 | 16.0 | 15.9 | 12.0 | 11.1 | 10.1 | 9.8 | 13.1 | 12.7 | 10.3
2006 | 10.4 | * | 0.4 | 0.9 | 16.7 | 15.7 | 11.6 | 11.2 | 9.7 | 9.9 | 12.9 | 12.5 | 10.3
2005 | 10.4 | * | 0.4 | 0.8 | 16.1 | 16.1 | 11.7 | 11.2 | 9.7 | 10.2 | 13.6 | 13.0 | 10.3
2004 | 10.1 | * | 0.3 | 0.7 | 15.6 | 15.3 | 11.4 | 11.0 | 9.8 | 10.1 | 13.3 | 12.7 | 10.0
2003 | 10.4 | * | 0.3 | 0.8 | 16.5 | 15.8 | 11.6 | 11.1 | 10.0 | 10.3 | 13.4 | 13.2 | 10.3
2002 | 10.5 | * | 0.4 | 0.8 | 16.6 | 15.6 | 12.2 | 10.8 | 10.2 | 10.8 | 14.4 | 13.2 | 10.5
2001 | 10.4 | * | 0.5 | 0.8 | 16.6 | 15.5 | 11.7 | 10.5 | 10.1 | 10.9 | 14.3 | 13.1 | 10.3
2000 | 10.2 | * | 0.3 | 0.9 | 16.8 | 14.5 | 11.9 | 10.5 | 9.4 | 10.6 | 13.9 | 14.2 | 10.2
1999 | 10.3 | * | 0.4 | 1.0 | 17.6 | 14.9 | 11.6 | 10.2 | 9.7 | 11.0 | 14.2 | 13.5 | 10.3

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

… Category not applicable.

^1^Data for age not stated included in “All ages” but not distributed among age groups.

^2^Death rates for ages younger than 1 year (based on population estimates) differ from infant mortality rates (based on live births); see Technical Notes.

^3^For computation method, see Technical Notes.

^4^COVID-19 became an official cause of death in 2020; rates for years before 2020 are not applicable.

^5^Data include September 11, 2001, related deaths for which death certificates were filed as of October 24, 2002; see Technical Notes from “Deaths: Final Data for 2001,” National Vital Statistics Reports, vol 53, no 3.

^6^For the list of ICD–10 codes included, see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 7 Number of deaths from 113 selected causes, Enterocolitis due to Clostridium difficile, COVID-19, dementia-related causes, drug-induced causes, alcohol-induced causes, and firearm-related injuries, by age: United States, 2022

[An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10); see Technical Notes in this report]

Cause of death (based on ICD–10) | Allages | Age group | | | | | | | | | | | Age notstated
Cause of death (based on ICD–10) | Allages | Younger than 1 | 1–4 | 5–14 | 15–24 | 25–34 | 35–44 | 45–54 | 55–64 | 65–74 | 75–84 | 85 and older | Age notstated
All causes | 3,279,857 | 20,553 | 4,156 | 6,239 | 35,232 | 74,369 | 111,605 | 183,284 | 417,541 | 668,581 | 824,903 | 933,291 | 103
Salmonella infections(A01–A02) | 82 | 5 | 3 | – | 2 | 2 | 2 | 6 | 11 | 16 | 25 | 10 | –
Shigellosis and amebiasis(A03,A06) | 17 | – | 3 | 1 | – | – | – | 3 | 2 | 6 | 1 | 1 | –
Certain other intestinal infections(A04,A07–A09) | 7,380 | 141 | 20 | 15 | 16 | 33 | 85 | 253 | 758 | 1,646 | 2,256 | 2,157 | –
Tuberculosis(A16–A19) | 565 | – | – | 2 | 5 | 21 | 25 | 41 | 128 | 138 | 123 | 82 | –
Respiratory tuberculosis(A16) | 391 | – | – | 1 | 5 | 11 | 21 | 24 | 85 | 93 | 85 | 66 | –
Other tuberculosis(A17–A19) | 174 | – | – | 1 | – | 10 | 4 | 17 | 43 | 45 | 38 | 16 | –
Whooping cough(A37) | 2 | 1 | – | – | – | – | – | 1 | – | – | – | – | –
Scarlet fever and erysipelas(A38,A46) | 3 | – | – | – | – | – | 1 | – | – | 1 | 1 | – | –
Meningococcal infection(A39) | 27 | 1 | 1 | 1 | 4 | 2 | 8 | 5 | 3 | 1 | 1 | – | –
Septicemia(A40–A41) | 42,261 | 123 | 60 | 59 | 113 | 447 | 1,024 | 2,488 | 6,167 | 10,623 | 11,723 | 9,433 | 1
Syphilis(A50–A53) | 61 | 15 | 1 | – | – | – | 4 | 7 | 5 | 12 | 10 | 7 | –
Acute poliomyelitis(A80) | – | – | – | – | – | – | – | – | – | – | – | – | –
Arthropod-borne viral encephalitis(A83–A84,A85.2) | 6 | – | – | – | – | – | – | – | 2 | 3 | 1 | – | –
Measles(B05) | – | – | – | – | – | – | – | – | – | – | – | – | –
Viral hepatitis(B15–B19) | 3,107 | 2 | 4 | – | 2 | 25 | 129 | 356 | 1,057 | 1,116 | 306 | 110 | –
Human immunodeficiency virus (HIV) disease(B20–B24) | 4,941 | 1 | – | – | 43 | 481 | 777 | 1,002 | 1,407 | 902 | 271 | 57 | –
Malaria(B50–B54) | 8 | – | – | – | 1 | – | 1 | 1 | 4 | – | 1 | – | –
Other and unspecified infectious and parasitic diseases and their sequelae(A00,A05,A20–A36,A42–A44,A48–A49,A54–A79,A81–A82,A85.0–A85.1,A85.8,A86–B04,B06–B09,B25–B49,B55–B99,U07.1) | 198,029 | 287 | 238 | 225 | 524 | 1,821 | 4,207 | 10,426 | 26,038 | 44,837 | 54,181 | 55,244 | 1
Malignant neoplasms(C00–C97) | 608,371 | 40 | 266 | 835 | 1,421 | 3,641 | 11,177 | 33,363 | 105,133 | 178,860 | 171,573 | 102,057 | 5
Malignant neoplasms of lip, oral cavity and pharynx(C00–C14) | 11,884 | – | – | 1 | 6 | 65 | 205 | 866 | 2,903 | 3,662 | 2,731 | 1,445 | –
Malignant neoplasm of esophagus(C15) | 16,016 | – | – | 1 | 6 | 33 | 226 | 1,040 | 3,456 | 5,524 | 4,099 | 1,629 | 2
Malignant neoplasm of stomach(C16) | 10,853 | – | 1 | – | 17 | 124 | 457 | 943 | 2,078 | 2,926 | 2,669 | 1,637 | 1
Malignant neoplasms of colon, rectum and anus(C18–C21) | 54,268 | – | – | 1 | 35 | 349 | 1,647 | 5,072 | 10,491 | 13,981 | 12,751 | 9,941 | –
Malignant neoplasms of liver and intrahepatic bile ducts(C22) | 28,937 | 4 | 9 | 16 | 26 | 122 | 373 | 1,354 | 6,098 | 10,692 | 7,237 | 3,006 | –
Malignant neoplasm of pancreas(C25) | 48,323 | 1 | – | 2 | 4 | 70 | 490 | 2,403 | 8,783 | 15,445 | 14,239 | 6,886 | –
Malignant neoplasm of larynx(C32) | 3,933 | – | – | – | 1 | 2 | 25 | 202 | 965 | 1,423 | 931 | 384 | –
Malignant neoplasms of trachea, bronchus and lung(C33–C34) | 131,982 | – | – | 1 | 12 | 118 | 771 | 4,484 | 24,394 | 44,583 | 40,755 | 16,863 | 1
Malignant melanoma of skin(C43) | 8,243 | – | 1 | – | 15 | 106 | 293 | 566 | 1,362 | 2,248 | 2,161 | 1,491 | –
Malignant neoplasm of breast(C50) | 42,672 | – | – | – | 7 | 383 | 1,856 | 4,083 | 8,165 | 10,747 | 9,864 | 7,567 | –
Malignant neoplasm of cervix uteri(C53) | 4,051 | – | – | – | 4 | 152 | 562 | 791 | 932 | 835 | 507 | 268 | –
Malignant neoplasms of corpus uteri and uterus, part unspecified(C54–C55) | 12,764 | – | – | – | – | 46 | 211 | 723 | 2,568 | 4,541 | 3,257 | 1,417 | 1
Malignant neoplasm of ovary(C56) | 13,214 | – | – | 2 | 33 | 104 | 287 | 1,061 | 2,717 | 3,835 | 3,549 | 1,626 | –
Malignant neoplasm of prostate(C61) | 33,363 | – | – | – | 2 | 2 | 21 | 357 | 2,777 | 8,385 | 11,604 | 10,215 | –
Malignant neoplasms of kidney and renal pelvis(C64–C65) | 14,488 | 2 | 12 | 29 | 22 | 57 | 198 | 919 | 2,633 | 4,214 | 4,012 | 2,390 | –
Malignant neoplasm of bladder(C67) | 17,334 | – | – | 1 | 1 | 20 | 100 | 330 | 1,640 | 3,910 | 5,870 | 5,462 | –
Malignant neoplasms of meninges, brain and other parts of central nervous system(C70–C72) | 17,937 | 9 | 56 | 302 | 243 | 446 | 823 | 1,692 | 3,881 | 5,365 | 3,708 | 1,412 | –
Malignant neoplasms of lymphoid, hematopoietic and related tissue(C81–C96) | 56,959 | 14 | 98 | 206 | 383 | 594 | 996 | 2,180 | 6,551 | 14,392 | 18,901 | 12,644 | –
Hodgkin disease(C81) | 1,056 | – | – | 2 | 12 | 48 | 59 | 102 | 140 | 259 | 273 | 161 | –
Non-Hodgkin lymphoma(C82–C85) | 19,794 | – | 3 | 20 | 55 | 150 | 320 | 776 | 2,335 | 5,058 | 6,670 | 4,407 | –
Leukemia(C91–C95) | 23,324 | 14 | 95 | 184 | 313 | 384 | 526 | 873 | 2,437 | 5,620 | 7,561 | 5,317 | –
Multiple myeloma and immunoproliferative neoplasms(C88,C90) | 12,616 | – | – | – | 1 | 10 | 87 | 425 | 1,617 | 3,420 | 4,340 | 2,716 | –
Other and unspecified malignant neoplasms of lymphoid, hematopoietic and related tissue(C96) | 169 | – | – | – | 2 | 2 | 4 | 4 | 22 | 35 | 57 | 43 | –
All other and unspecified malignant neoplasms(C17,C23–C24,C26–C31,C37–C41,C44–C49,C51–C52,C57–C60,C62–C63,C66,C68–C69,C73–C80,C97) | 81,150 | 10 | 89 | 273 | 604 | 848 | 1,636 | 4,297 | 12,739 | 22,152 | 22,728 | 15,774 | –
In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 16,034 | 32 | 37 | 51 | 74 | 106 | 256 | 503 | 1,437 | 3,376 | 5,216 | 4,946 | –
Anemias(D50–D64) | 6,021 | 5 | 13 | 31 | 88 | 153 | 218 | 289 | 612 | 1,110 | 1,512 | 1,990 | –
Diabetes mellitus(E10–E14) | 101,209 | 2 | 7 | 48 | 324 | 1,188 | 2,879 | 7,364 | 17,410 | 26,963 | 26,388 | 18,634 | 2
Nutritional deficiencies(E40–E64) | 21,020 | 13 | 10 | 4 | 13 | 47 | 113 | 282 | 1,010 | 2,728 | 5,458 | 11,342 | –
Malnutrition(E40–E46) | 20,552 | 8 | 9 | 4 | 13 | 46 | 104 | 258 | 945 | 2,632 | 5,366 | 11,167 | –
Other nutritional deficiencies(E50–E64) | 468 | 5 | 1 | – | – | 1 | 9 | 24 | 65 | 96 | 92 | 175 | –
Meningitis(G00,G03) | 604 | 43 | 18 | 17 | 15 | 29 | 59 | 61 | 93 | 130 | 96 | 43 | –
Parkinson disease(G20–G21) | 39,915 | 1 | – | – | – | 6 | 12 | 86 | 879 | 6,424 | 17,886 | 14,621 | –
Alzheimer disease(G30) | 120,122 | – | – | – | – | – | 6 | 111 | 1,480 | 9,005 | 36,133 | 73,387 | –
Major cardiovascular diseases(I00–I78) | 936,436 | 340 | 156 | 335 | 1,078 | 4,765 | 15,656 | 40,956 | 107,984 | 182,806 | 242,054 | 340,276 | 30
Diseases of heart(I00–I09,I11,I13,I20–I51) | 702,880 | 241 | 103 | 218 | 848 | 3,789 | 12,258 | 32,298 | 85,733 | 140,475 | 178,108 | 248,782 | 27
Acute rheumatic fever and chronic rheumatic heart diseases(I00–I09) | 4,294 | 1 | 1 | 1 | 10 | 61 | 127 | 196 | 457 | 818 | 1,215 | 1,407 | –
Hypertensive heart disease(I11) | 72,070 | – | – | 2 | 58 | 539 | 2,146 | 4,701 | 10,137 | 13,199 | 14,820 | 26,465 | 3
Hypertensive heart and renal disease(I13) | 16,091 | – | – | 1 | 2 | 45 | 158 | 456 | 1,050 | 2,279 | 4,288 | 7,812 | –
Ischemic heart diseases(I20–I25) | 371,506 | 11 | 5 | 8 | 102 | 990 | 4,956 | 17,223 | 50,365 | 83,121 | 97,826 | 116,879 | 20
Acute myocardial infarction(I21–I22) | 103,905 | 4 | 1 | 3 | 47 | 394 | 1,877 | 6,109 | 16,744 | 25,801 | 27,512 | 25,409 | 4
Other acute ischemic heart diseases(I24) | 4,823 | 2 | 1 | 1 | 3 | 21 | 83 | 308 | 823 | 1,146 | 1,182 | 1,253 | –
Other forms of chronic ischemic heart disease(I20,I25) | 262,778 | 5 | 3 | 4 | 52 | 575 | 2,996 | 10,806 | 32,798 | 56,174 | 69,132 | 90,217 | 16
Atherosclerotic cardiovascular disease, so described(I25.0) | 81,672 | – | 1 | 1 | 21 | 351 | 1,767 | 6,079 | 16,731 | 22,134 | 17,820 | 16,755 | 12
All other forms of chronic ischemic heart disease(I20,I25.1–I25.9) | 181,106 | 5 | 2 | 3 | 31 | 224 | 1,229 | 4,727 | 16,067 | 34,040 | 51,312 | 73,462 | 4
Other heart diseases(I26–I51) | 238,919 | 229 | 97 | 206 | 676 | 2,154 | 4,871 | 9,722 | 23,724 | 41,058 | 59,959 | 96,219 | 4
Acute and subacute endocarditis(I33) | 1,803 | 2 | – | 3 | 17 | 109 | 177 | 213 | 323 | 403 | 359 | 197 | –
Diseases of pericardium and acute myocarditis(I30–I31,I40) | 1,237 | 9 | 3 | 18 | 22 | 43 | 65 | 101 | 182 | 292 | 283 | 219 | –
Heart failure(I50) | 87,941 | 13 | 5 | 8 | 43 | 247 | 714 | 1,962 | 5,820 | 12,599 | 22,750 | 43,779 | 1
All other forms of heart disease(I26–I28,I34–I38,I42–I49,I51) | 147,938 | 205 | 89 | 177 | 594 | 1,755 | 3,915 | 7,446 | 17,399 | 27,764 | 36,567 | 52,024 | 3
Essential hypertension and hypertensive renal disease(I10,I12,I15) | 43,293 | 3 | – | 2 | 24 | 175 | 697 | 1,832 | 4,982 | 8,315 | 10,790 | 16,472 | 1
Cerebrovascular diseases(I60–I69) | 165,393 | 87 | 49 | 100 | 157 | 599 | 2,150 | 5,563 | 14,173 | 28,384 | 46,421 | 67,708 | 2
Atherosclerosis(I70) | 3,936 | 2 | 1 | – | – | 2 | 10 | 68 | 291 | 684 | 999 | 1,879 | –
Other diseases of circulatory system(I71–I78) | 20,934 | 7 | 3 | 15 | 49 | 200 | 541 | 1,195 | 2,805 | 4,948 | 5,736 | 5,435 | –
Aortic aneurysm and dissection(I71) | 9,999 | 1 | – | 7 | 29 | 128 | 357 | 747 | 1,435 | 2,225 | 2,762 | 2,308 | –
Other diseases of arteries, arterioles and capillaries(I72–I78) | 10,935 | 6 | 3 | 8 | 20 | 72 | 184 | 448 | 1,370 | 2,723 | 2,974 | 3,127 | –
Other disorders of circulatory system(I80–I99) | 5,216 | 16 | 1 | 3 | 60 | 191 | 480 | 613 | 926 | 1,028 | 1,009 | 888 | 1
Influenza and pneumonia(J09–J18) | 47,052 | 154 | 129 | 131 | 168 | 490 | 985 | 1,905 | 5,067 | 9,408 | 12,774 | 15,840 | 1
Influenza(J09–J11) | 5,944 | 12 | 53 | 76 | 61 | 112 | 217 | 310 | 771 | 1,147 | 1,475 | 1,710 | –
Pneumonia(J12–J18) | 41,108 | 142 | 76 | 55 | 107 | 378 | 768 | 1,595 | 4,296 | 8,261 | 11,299 | 14,130 | 1
Other acute lower respiratory infections(J20–J22,U04) | 278 | 43 | 24 | 4 | 2 | 3 | 4 | 8 | 21 | 42 | 43 | 84 | –
Acute bronchitis and bronchiolitis(J20–J21) | 182 | 40 | 22 | 3 | 1 | 2 | 2 | 3 | 11 | 25 | 25 | 48 | –
Other and unspecified acute lower respiratory infections(J22,U04) | 96 | 3 | 2 | 1 | 1 | 1 | 2 | 5 | 10 | 17 | 18 | 36 | –
Chronic lower respiratory diseases(J40–J47) | 147,382 | 10 | 39 | 106 | 197 | 368 | 732 | 2,987 | 17,138 | 38,712 | 49,746 | 37,345 | 2
Bronchitis, chronic and unspecified(J40–J42) | 358 | 4 | 7 | 2 | 4 | 3 | 3 | 13 | 44 | 76 | 82 | 120 | –
Emphysema(J43) | 7,905 | 1 | – | 1 | 1 | 2 | 34 | 179 | 983 | 2,205 | 2,716 | 1,783 | –
Asthma(J45–J46) | 3,602 | 2 | 26 | 95 | 181 | 322 | 366 | 480 | 580 | 574 | 487 | 489 | –
Other chronic lower respiratory diseases(J44,J47) | 135,517 | 3 | 6 | 8 | 11 | 41 | 329 | 2,315 | 15,531 | 35,857 | 46,461 | 34,953 | 2
Pneumoconioses and chemical effects(J60–J66,J68,U07.0) | 562 | – | – | 2 | 1 | 3 | 5 | 13 | 39 | 135 | 196 | 168 | –
Pneumonitis due to solids and liquids(J69) | 20,052 | 8 | 5 | 7 | 49 | 132 | 278 | 599 | 1,763 | 3,647 | 5,892 | 7,672 | –
Other diseases of respiratory system(J00–J06,J30–J39,J67,J70–J98) | 48,082 | 172 | 103 | 99 | 143 | 319 | 641 | 1,584 | 5,054 | 11,010 | 15,433 | 13,522 | 2
Peptic ulcer(K25–K28) | 4,105 | – | 1 | 2 | 8 | 34 | 116 | 285 | 624 | 995 | 1,069 | 971 | –
Diseases of appendix(K35–K38) | 487 | 3 | 1 | 4 | 4 | 11 | 20 | 36 | 81 | 91 | 115 | 121 | –
Hernia(K40–K46) | 2,712 | 10 | 9 | 5 | 6 | 9 | 49 | 126 | 316 | 528 | 699 | 955 | –
Chronic liver disease and cirrhosis(K70,K73–K74) | 54,803 | 1 | 2 | 2 | 58 | 1,786 | 5,501 | 9,401 | 16,484 | 13,178 | 6,428 | 1,959 | 3
Alcoholic liver disease(K70) | 30,910 | – | – | – | 46 | 1,508 | 4,335 | 6,688 | 10,362 | 6,017 | 1,683 | 270 | 1
Other chronic liver disease and cirrhosis(K73–K74) | 23,893 | 1 | 2 | 2 | 12 | 278 | 1,166 | 2,713 | 6,122 | 7,161 | 4,745 | 1,689 | 2
Cholelithiasis and other disorders of gallbladder(K80–K82) | 4,483 | 1 | – | 1 | 18 | 21 | 48 | 131 | 396 | 904 | 1,360 | 1,603 | –
Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 57,937 | 38 | 4 | 11 | 64 | 358 | 1,029 | 2,679 | 6,668 | 12,948 | 17,003 | 17,135 | –
Acute and rapidly progressive nephritic and nephrotic syndrome(N00–N01,N04) | 810 | 2 | 1 | 4 | 2 | 4 | 12 | 30 | 80 | 135 | 255 | 285 | –
Chronic glomerulonephritis, nephritis and nephropathy not specified as acute or chronic, and renal sclerosis unspecified(N02–N03,N05–N07,N26) | 330 | – | – | 2 | 5 | 14 | 20 | 38 | 47 | 85 | 75 | 44 | –
Renal failure(N17–N19) | 56,756 | 36 | 3 | 5 | 57 | 340 | 995 | 2,608 | 6,535 | 12,718 | 16,661 | 16,798 | –
Other disorders of kidney(N25,N27) | 41 | – | – | – | – | – | 2 | 3 | 6 | 10 | 12 | 8 | –
Infections of kidney(N10–N12,N13.6,N15.1) | 1,205 | 4 | 3 | 3 | 5 | 15 | 37 | 78 | 142 | 285 | 356 | 276 | 1
Hyperplasia of prostate(N40) | 839 | – | – | – | – | – | – | 8 | 39 | 103 | 244 | 445 | –
Inflammatory diseases of female pelvic organs(N70–N76) | 232 | – | – | – | 7 | 3 | 19 | 15 | 44 | 50 | 47 | 47 | –
Pregnancy, childbirth and the puerperium(O00–O99) | 1,263 | … | … | 5 | 164 | 591 | 489 | 12 | 1 | 1 | – | – | –
Pregnancy with abortive outcome(O00–O07) | 33 | … | … | – | 5 | 18 | 10 | – | – | – | – | – | –
Other complications of pregnancy, childbirth and the puerperium(O10–O99) | 1,230 | … | … | 5 | 159 | 573 | 479 | 12 | 1 | 1 | – | – | –
Certain conditions originating in the perinatal period(P00–P96) | 10,203 | 10,068 | 62 | 28 | 15 | 7 | 5 | 3 | 5 | 5 | 1 | 4 | –
Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 10,149 | 3,970 | 441 | 446 | 412 | 490 | 542 | 783 | 1,310 | 842 | 559 | 354 | –
Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified(R00–R99) | 34,110 | 2,691 | 305 | 133 | 598 | 1,334 | 1,699 | 2,099 | 3,634 | 5,003 | 6,010 | 10,582 | 22
All other diseases(residual) | 410,973 | 563 | 417 | 802 | 1,995 | 5,670 | 10,832 | 18,951 | 40,782 | 68,055 | 103,290 | 159,609 | 7
Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 227,039 | 1,354 | 1,288 | 1,652 | 14,669 | 33,058 | 36,972 | 31,394 | 34,017 | 23,150 | 22,392 | 27,074 | 19
Transport accidents(V01–V99,Y85) | 49,178 | 80 | 386 | 945 | 7,215 | 8,797 | 7,586 | 6,545 | 7,273 | 5,482 | 3,435 | 1,431 | 3
Motor vehicle accidents(V02–V04,V09.0,V09.2,V12–V14,V19.0–V19.2,V19.4–V19.6,V20–V79,V80.3–V80.5,V81.0–V81.1,V82.0–V82.1,V83–V86,V87.0–V87.8,V88.0–V88.8, V89.0,V89.2) | 46,027 | 79 | 366 | 900 | 6,997 | 8,406 | 7,084 | 6,080 | 6,567 | 4,949 | 3,219 | 1,377 | 3
Other land transport accidents(V01,V05–V06,V09.1,V09.3–V09.9,V10–V11,V15–V18,V19.3,V19.8–V19.9,V80.0–V80.2,V80.6–V80.9,V81.2–V81.9,V82.2–V82.9,V87.9, V88.9,V89.1,V89.3,V89.9) | 1,195 | 1 | 13 | 19 | 106 | 184 | 207 | 157 | 240 | 174 | 74 | 20 | –
Water, air and space, and other and unspecified transport accidents and their sequelae(V90–V99,Y85) | 1,956 | – | 7 | 26 | 112 | 207 | 295 | 308 | 466 | 359 | 142 | 34 | –
Nontransport accidents(W00–X59,Y86) | 177,861 | 1,274 | 902 | 707 | 7,454 | 24,261 | 29,386 | 24,849 | 26,744 | 17,668 | 18,957 | 25,643 | 16
Falls(W00–W19) | 46,630 | 6 | 21 | 21 | 149 | 383 | 682 | 1,200 | 3,247 | 6,698 | 13,396 | 20,825 | 2
Accidental discharge of firearms(W32–W34) | 463 | – | 49 | 35 | 120 | 69 | 55 | 42 | 36 | 31 | 18 | 8 | –
Accidental drowning and submersion(W65–W74) | 4,168 | 39 | 458 | 222 | 454 | 500 | 502 | 421 | 562 | 552 | 321 | 135 | 2
Accidental exposure to smoke, fire and flames(X00–X09) | 3,478 | 15 | 85 | 158 | 125 | 180 | 232 | 311 | 689 | 864 | 555 | 264 | –
Accidental poisoning and exposure to noxious substances(X40–X49) | 102,958 | 28 | 75 | 99 | 6,205 | 22,295 | 26,767 | 21,364 | 19,334 | 5,924 | 697 | 159 | 11
Other and unspecified nontransport accidents and their sequelae(W20–W31,W35–W64,W75–W99,X10–X39,X50–X59,Y86) | 20,164 | 1,186 | 214 | 172 | 401 | 834 | 1,148 | 1,511 | 2,876 | 3,599 | 3,970 | 4,252 | 1
Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 49,476 | … | … | 502 | 6,040 | 8,663 | 8,185 | 7,781 | 7,864 | 5,396 | 3,549 | 1,493 | 3
Intentional self-harm (suicide) by discharge of firearms(X72–X74) | 27,032 | … | … | 180 | 3,246 | 4,230 | 3,759 | 3,838 | 4,412 | 3,536 | 2,686 | 1,145 | –
Intentional self-harm (suicide) by other and unspecified means and their sequelae(*U03,X60–X71,X75–X84,Y87.0) | 22,444 | … | … | 322 | 2,794 | 4,433 | 4,426 | 3,943 | 3,452 | 1,860 | 863 | 348 | 3
Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 24,849 | 252 | 343 | 546 | 6,262 | 6,712 | 4,765 | 2,740 | 1,824 | 877 | 399 | 127 | 2
Assault (homicide) by discharge of firearms(*U01.4,X93–X95) | 19,651 | 16 | 77 | 395 | 5,814 | 5,836 | 3,861 | 1,947 | 1,080 | 422 | 163 | 40 | –
Assault (homicide) by other and unspecified means and their sequelae(*U01.0–*U01.3,*U01.5–*U01.9,*U02,X85–X92,X96–Y09,Y87.1) | 5,198 | 236 | 266 | 151 | 448 | 876 | 904 | 793 | 744 | 455 | 236 | 87 | 2
Legal intervention(Y35,Y89.0) | 810 | – | – | 1 | 120 | 248 | 209 | 134 | 70 | 23 | 5 | – | –
Events of undetermined intent(Y10–Y34,Y87.2,Y89.9) | 5,604 | 123 | 127 | 98 | 403 | 1,014 | 1,174 | 1,025 | 959 | 458 | 153 | 69 | 1
Discharge of firearms, undetermined intent(Y22–Y24) | 415 | – | 14 | 18 | 103 | 94 | 62 | 45 | 41 | 20 | 14 | 4 | –
Other and unspecified events of undetermined intent and their sequelae(Y10–Y21,Y25–Y34,Y87.2,Y89.9) | 5,189 | 123 | 113 | 80 | 300 | 920 | 1,112 | 980 | 918 | 438 | 139 | 65 | 1
Operations of war and their sequelae(Y36,Y89.1) | 7 | – | – | – | – | – | 2 | 1 | – | 1 | 3 | – | –
Complications of medical and surgical care(Y40–Y84,Y88) | 3,726 | 20 | 15 | 22 | 41 | 72 | 148 | 289 | 653 | 1,003 | 912 | 551 | –
Enterocolitis due to Clostridium difficile(A04.7)^1^ | 4,231 | 1 | – | – | 5 | 10 | 46 | 135 | 419 | 989 | 1,383 | 1,243 | –
COVID-19(U07.1)^1^ | 186,552 | 141 | 101 | 131 | 447 | 1,640 | 3,841 | 9,678 | 24,252 | 42,062 | 51,188 | 53,070 | 1
Dementia-related causes^1^ | 292,881 | 10 | 16 | 23 | 9 | 16 | 52 | 371 | 3,946 | 22,770 | 83,437 | 182,229 | 2
Drug-induced deaths^1^ | 112,109 | 72 | 182 | 160 | 6,782 | 23,565 | 28,427 | 23,169 | 21,350 | 6,983 | 1,103 | 304 | 12
Drug overdose deaths^1^ | 107,941 | 71 | 182 | 160 | 6,696 | 23,029 | 27,583 | 22,352 | 20,252 | 6,434 | 930 | 241 | 11
Alcohol-induced deaths^1^ | 51,191 | 1 | – | 1 | 200 | 2,992 | 7,429 | 10,852 | 16,718 | 9,745 | 2,752 | 496 | 5
Firearm-related injuries^1^ | 48,204 | 16 | 140 | 628 | 9,363 | 10,436 | 7,904 | 5,981 | 5,625 | 4,030 | 2,884 | 1,197 | –

– Quantity zero.

… Category not applicable.

^1^Included in selected categories above. For list of ICD–10 codes included, see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 8 Death rate for 113 selected causes, Enterocolitis due to Clostridium difficile, COVID-19, dementia-related causes, drug-induced causes, alcohol-induced causes, and firearm-related injuries, by age: United States, 2022

[Rates are on an annual basis per 100,000 population in specified group; see Technical Notes in this report. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10); see Technical Notes]

Cause of death (based on ICD–10) | Allages^1^ | Age group
Cause of death (based on ICD–10) | Allages^1^ | Younger than 1^2^ | 1–4 | 5–14 | 15–24 | 25–34 | 35–44 | 45–54 | 55–64 | 65–74 | 75–84 | 85 and older
All causes | 984.1 | 558.0 | 28.0 | 15.3 | 79.5 | 163.4 | 255.4 | 453.3 | 992.1 | 1,978.7 | 4,708.2 | 14,389.6
Salmonella infections(A01–A02) | 0.0 | * | * | * | * | * | * | * | * | * | 0.1 | *
Shigellosis and amebiasis(A03,A06) | * | * | * | * | * | * | * | * | * | * | * | *
Certain other intestinal infections(A04,A07–A09) | 2.2 | 3.8 | 0.1 | * | * | 0.1 | 0.2 | 0.6 | 1.8 | 4.9 | 12.9 | 33.3
Tuberculosis(A16–A19) | 0.2 | * | * | * | * | 0.0 | 0.1 | 0.1 | 0.3 | 0.4 | 0.7 | 1.3
Respiratory tuberculosis(A16) | 0.1 | * | * | * | * | * | 0.0 | 0.1 | 0.2 | 0.3 | 0.5 | 1.0
Other tuberculosis(A17–A19) | 0.1 | * | * | * | * | * | * | * | 0.1 | 0.1 | 0.2 | *
Whooping cough(A37) | * | * | * | * | * | * | * | * | * | * | * | *
Scarlet fever and erysipelas(A38,A46) | * | * | * | * | * | * | * | * | * | * | * | *
Meningococcal infection(A39) | 0.0 | * | * | * | * | * | * | * | * | * | * | *
Septicemia(A40–A41) | 12.7 | 3.3 | 0.4 | 0.1 | 0.3 | 1.0 | 2.3 | 6.2 | 14.7 | 31.4 | 66.9 | 145.4
Syphilis(A50–A53) | 0.0 | * | * | * | * | * | * | * | * | * | * | *
Acute poliomyelitis(A80) | * | * | * | * | * | * | * | * | * | * | * | *
Arthropod-borne viral encephalitis(A83–A84,A85.2) | * | * | * | * | * | * | * | * | * | * | * | *
Measles(B05) | * | * | * | * | * | * | * | * | * | * | * | *
Viral hepatitis(B15–B19) | 0.9 | * | * | * | * | 0.1 | 0.3 | 0.9 | 2.5 | 3.3 | 1.7 | 1.7
Human immunodeficiency virus (HIV) disease(B20–B24) | 1.5 | * | * | * | 0.1 | 1.1 | 1.8 | 2.5 | 3.3 | 2.7 | 1.5 | 0.9
Malaria(B50–B54) | * | * | * | * | * | * | * | * | * | * | * | *
Other and unspecified infectious and parasitic diseases and their sequelae(A00,A05,A20–A36,A42–A44,A48–A49,A54–A79,A81–A82,A85.0–A85.1,A85.8,A86–B04,B06–B09,B25–B49,B55–B99,U07.1) | 59.4 | 7.8 | 1.6 | 0.6 | 1.2 | 4.0 | 9.6 | 25.8 | 61.9 | 132.7 | 309.2 | 851.8
Malignant neoplasms(C00–C97) | 182.5 | 1.1 | 1.8 | 2.0 | 3.2 | 8.0 | 25.6 | 82.5 | 249.8 | 529.4 | 979.3 | 1,573.5
Malignant neoplasms of lip, oral cavity and pharynx(C00–C14) | 3.6 | * | * | * | * | 0.1 | 0.5 | 2.1 | 6.9 | 10.8 | 15.6 | 22.3
Malignant neoplasm of esophagus(C15) | 4.8 | * | * | * | * | 0.1 | 0.5 | 2.6 | 8.2 | 16.3 | 23.4 | 25.1
Malignant neoplasm of stomach(C16) | 3.3 | * | * | * | * | 0.3 | 1.0 | 2.3 | 4.9 | 8.7 | 15.2 | 25.2
Malignant neoplasms of colon, rectum and anus(C18–C21) | 16.3 | * | * | * | 0.1 | 0.8 | 3.8 | 12.5 | 24.9 | 41.4 | 72.8 | 153.3
Malignant neoplasms of liver and intrahepatic bile ducts(C22) | 8.7 | * | * | * | 0.1 | 0.3 | 0.9 | 3.3 | 14.5 | 31.6 | 41.3 | 46.3
Malignant neoplasm of pancreas(C25) | 14.5 | * | * | * | * | 0.2 | 1.1 | 5.9 | 20.9 | 45.7 | 81.3 | 106.2
Malignant neoplasm of larynx(C32) | 1.2 | * | * | * | * | * | 0.1 | 0.5 | 2.3 | 4.2 | 5.3 | 5.9
Malignant neoplasms of trachea, bronchus and lung(C33–C34) | 39.6 | * | * | * | * | 0.3 | 1.8 | 11.1 | 58.0 | 131.9 | 232.6 | 260.0
Malignant melanoma of skin(C43) | 2.5 | * | * | * | * | 0.2 | 0.7 | 1.4 | 3.2 | 6.7 | 12.3 | 23.0
Malignant neoplasm of breast(C50) | 12.8 | * | * | * | * | 0.8 | 4.2 | 10.1 | 19.4 | 31.8 | 56.3 | 116.7
Malignant neoplasm of cervix uteri(C53) | 1.2 | * | * | * | * | 0.3 | 1.3 | 2.0 | 2.2 | 2.5 | 2.9 | 4.1
Malignant neoplasms of corpus uteri and uterus, part unspecified(C54–C55) | 3.8 | * | * | * | * | 0.1 | 0.5 | 1.8 | 6.1 | 13.4 | 18.6 | 21.8
Malignant neoplasm of ovary(C56) | 4.0 | * | * | * | 0.1 | 0.2 | 0.7 | 2.6 | 6.5 | 11.4 | 20.3 | 25.1
Malignant neoplasm of prostate(C61) | 10.0 | * | * | * | * | * | 0.0 | 0.9 | 6.6 | 24.8 | 66.2 | 157.5
Malignant neoplasms of kidney and renal pelvis(C64–C65) | 4.3 | * | * | 0.1 | 0.0 | 0.1 | 0.5 | 2.3 | 6.3 | 12.5 | 22.9 | 36.8
Malignant neoplasm of bladder(C67) | 5.2 | * | * | * | * | 0.0 | 0.2 | 0.8 | 3.9 | 11.6 | 33.5 | 84.2
Malignant neoplasms of meninges, brain and other parts of central nervous system(C70–C72) | 5.4 | * | 0.4 | 0.7 | 0.5 | 1.0 | 1.9 | 4.2 | 9.2 | 15.9 | 21.2 | 21.8
Malignant neoplasms of lymphoid, hematopoietic and related tissue(C81–C96) | 17.1 | * | 0.7 | 0.5 | 0.9 | 1.3 | 2.3 | 5.4 | 15.6 | 42.6 | 107.9 | 194.9
Hodgkin disease(C81) | 0.3 | * | * | * | * | 0.1 | 0.1 | 0.3 | 0.3 | 0.8 | 1.6 | 2.5
Non-Hodgkin lymphoma(C82–C85) | 5.9 | * | * | 0.0 | 0.1 | 0.3 | 0.7 | 1.9 | 5.5 | 15.0 | 38.1 | 67.9
Leukemia(C91–C95) | 7.0 | * | 0.6 | 0.4 | 0.7 | 0.8 | 1.2 | 2.2 | 5.8 | 16.6 | 43.2 | 82.0
Multiple myeloma and immunoproliferative neoplasms(C88,C90) | 3.8 | * | * | * | * | * | 0.2 | 1.1 | 3.8 | 10.1 | 24.8 | 41.9
Other and unspecified malignant neoplasms of lymphoid, hematopoietic and related tissue(C96) | 0.1 | * | * | * | * | * | * | * | 0.1 | 0.1 | 0.3 | 0.7
All other and unspecified malignant neoplasms(C17,C23–C24,C26–C31,C37–C41,C44–C49,C51–C52,C57–C60,C62–C63,C66,C68–C69,C73–C80,C97) | 24.3 | * | 0.6 | 0.7 | 1.4 | 1.9 | 3.7 | 10.6 | 30.3 | 65.6 | 129.7 | 243.2
In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 4.8 | 0.9 | 0.2 | 0.1 | 0.2 | 0.2 | 0.6 | 1.2 | 3.4 | 10.0 | 29.8 | 76.3
Anemias(D50–D64) | 1.8 | * | * | 0.1 | 0.2 | 0.3 | 0.5 | 0.7 | 1.5 | 3.3 | 8.6 | 30.7
Diabetes mellitus(E10–E14) | 30.4 | * | * | 0.1 | 0.7 | 2.6 | 6.6 | 18.2 | 41.4 | 79.8 | 150.6 | 287.3
Nutritional deficiencies(E40–E64) | 6.3 | * | * | * | * | 0.1 | 0.3 | 0.7 | 2.4 | 8.1 | 31.2 | 174.9
Malnutrition(E40–E46) | 6.2 | * | * | * | * | 0.1 | 0.2 | 0.6 | 2.2 | 7.8 | 30.6 | 172.2
Other nutritional deficiencies(E50–E64) | 0.1 | * | * | * | * | * | * | 0.1 | 0.2 | 0.3 | 0.5 | 2.7
Meningitis(G00,G03) | 0.2 | 1.2 | * | * | * | 0.1 | 0.1 | 0.2 | 0.2 | 0.4 | 0.5 | 0.7
Parkinson disease(G20–G21) | 12.0 | * | * | * | * | * | * | 0.2 | 2.1 | 19.0 | 102.1 | 225.4
Alzheimer disease(G30) | 36.0 | * | * | * | * | * | * | 0.3 | 3.5 | 26.7 | 206.2 | 1,131.5
Major cardiovascular diseases(I00–I78) | 281.0 | 9.2 | 1.1 | 0.8 | 2.4 | 10.5 | 35.8 | 101.3 | 256.6 | 541.0 | 1,381.5 | 5,246.4
Diseases of heart(I00–I09,I11,I13,I20–I51) | 210.9 | 6.5 | 0.7 | 0.5 | 1.9 | 8.3 | 28.1 | 79.9 | 203.7 | 415.7 | 1,016.6 | 3,835.8
Acute rheumatic fever and chronic rheumatic heart diseases(I00–I09) | 1.3 | * | * | * | * | 0.1 | 0.3 | 0.5 | 1.1 | 2.4 | 6.9 | 21.7
Hypertensive heart disease(I11) | 21.6 | * | * | * | 0.1 | 1.2 | 4.9 | 11.6 | 24.1 | 39.1 | 84.6 | 408.0
Hypertensive heart and renal disease(I13) | 4.8 | * | * | * | * | 0.1 | 0.4 | 1.1 | 2.5 | 6.7 | 24.5 | 120.4
Ischemic heart diseases(I20–I25) | 111.5 | * | * | * | 0.2 | 2.2 | 11.3 | 42.6 | 119.7 | 246.0 | 558.4 | 1,802.1
Acute myocardial infarction(I21–I22) | 31.2 | * | * | * | 0.1 | 0.9 | 4.3 | 15.1 | 39.8 | 76.4 | 157.0 | 391.8
Other acute ischemic heart diseases(I24) | 1.4 | * | * | * | * | 0.0 | 0.2 | 0.8 | 2.0 | 3.4 | 6.7 | 19.3
Other forms of chronic ischemic heart disease(I20,I25) | 78.8 | * | * | * | 0.1 | 1.3 | 6.9 | 26.7 | 77.9 | 166.3 | 394.6 | 1,391.0
Atherosclerotic cardiovascular disease, so described(I25.0) | 24.5 | * | * | * | 0.0 | 0.8 | 4.0 | 15.0 | 39.8 | 65.5 | 101.7 | 258.3
All other forms of chronic ischemic heart disease(I20,I25.1–I25.9) | 54.3 | * | * | * | 0.1 | 0.5 | 2.8 | 11.7 | 38.2 | 100.7 | 292.9 | 1,132.6
Other heart diseases(I26–I51) | 71.7 | 6.2 | 0.7 | 0.5 | 1.5 | 4.7 | 11.1 | 24.0 | 56.4 | 121.5 | 342.2 | 1,483.5
Acute and subacute endocarditis(I33) | 0.5 | * | * | * | * | 0.2 | 0.4 | 0.5 | 0.8 | 1.2 | 2.0 | 3.0
Diseases of pericardium and acute myocarditis(I30–I31,I40) | 0.4 | * | * | * | 0.0 | 0.1 | 0.1 | 0.2 | 0.4 | 0.9 | 1.6 | 3.4
Heart failure(I50) | 26.4 | * | * | * | 0.1 | 0.5 | 1.6 | 4.9 | 13.8 | 37.3 | 129.8 | 675.0
All other forms of heart disease(I26–I28,I34–I38,I42–I49,I51) | 44.4 | 5.6 | 0.6 | 0.4 | 1.3 | 3.9 | 9.0 | 18.4 | 41.3 | 82.2 | 208.7 | 802.1
Essential hypertension and hypertensive renal disease(I10,I12,I15) | 13.0 | * | * | * | 0.1 | 0.4 | 1.6 | 4.5 | 11.8 | 24.6 | 61.6 | 254.0
Cerebrovascular diseases(I60–I69) | 49.6 | 2.4 | 0.3 | 0.2 | 0.4 | 1.3 | 4.9 | 13.8 | 33.7 | 84.0 | 265.0 | 1,043.9
Atherosclerosis(I70) | 1.2 | * | * | * | * | * | * | 0.2 | 0.7 | 2.0 | 5.7 | 29.0
Other diseases of circulatory system(I71–I78) | 6.3 | * | * | * | 0.1 | 0.4 | 1.2 | 3.0 | 6.7 | 14.6 | 32.7 | 83.8
Aortic aneurysm and dissection(I71) | 3.0 | * | * | * | 0.1 | 0.3 | 0.8 | 1.8 | 3.4 | 6.6 | 15.8 | 35.6
Other diseases of arteries, arterioles and capillaries(I72–I78) | 3.3 | * | * | * | 0.0 | 0.2 | 0.4 | 1.1 | 3.3 | 8.1 | 17.0 | 48.2
Other disorders of circulatory system(I80–I99) | 1.6 | * | * | * | 0.1 | 0.4 | 1.1 | 1.5 | 2.2 | 3.0 | 5.8 | 13.7
Influenza and pneumonia(J09–J18) | 14.1 | 4.2 | 0.9 | 0.3 | 0.4 | 1.1 | 2.3 | 4.7 | 12.0 | 27.8 | 72.9 | 244.2
Influenza(J09–J11) | 1.8 | * | 0.4 | 0.2 | 0.1 | 0.2 | 0.5 | 0.8 | 1.8 | 3.4 | 8.4 | 26.4
Pneumonia(J12–J18) | 12.3 | 3.9 | 0.5 | 0.1 | 0.2 | 0.8 | 1.8 | 3.9 | 10.2 | 24.4 | 64.5 | 217.9
Other acute lower respiratory infections(J20–J22,U04) | 0.1 | 1.2 | 0.2 | * | * | * | * | * | 0.0 | 0.1 | 0.2 | 1.3
Acute bronchitis and bronchiolitis(J20–J21) | 0.1 | 1.1 | 0.1 | * | * | * | * | * | * | 0.1 | 0.1 | 0.7
Other and unspecified acute lower respiratory infections(J22,U04) | 0.0 | * | * | * | * | * | * | * | * | * | * | 0.6
Chronic lower respiratory diseases(J40–J47) | 44.2 | * | 0.3 | 0.3 | 0.4 | 0.8 | 1.7 | 7.4 | 40.7 | 114.6 | 283.9 | 575.8
Bronchitis, chronic and unspecified(J40–J42) | 0.1 | * | * | * | * | * | * | * | 0.1 | 0.2 | 0.5 | 1.9
Emphysema(J43) | 2.4 | * | * | * | * | * | 0.1 | 0.4 | 2.3 | 6.5 | 15.5 | 27.5
Asthma(J45–J46) | 1.1 | * | 0.2 | 0.2 | 0.4 | 0.7 | 0.8 | 1.2 | 1.4 | 1.7 | 2.8 | 7.5
Other chronic lower respiratory diseases(J44,J47) | 40.7 | * | * | * | * | 0.1 | 0.8 | 5.7 | 36.9 | 106.1 | 265.2 | 538.9
Pneumoconioses and chemical effects(J60–J66,J68,U07.0) | 0.2 | * | * | * | * | * | * | * | 0.1 | 0.4 | 1.1 | 2.6
Pneumonitis due to solids and liquids(J69) | 6.0 | * | * | * | 0.1 | 0.3 | 0.6 | 1.5 | 4.2 | 10.8 | 33.6 | 118.3
Other diseases of respiratory system(J00–J06,J30–J39,J67,J70–J98) | 14.4 | 4.7 | 0.7 | 0.2 | 0.3 | 0.7 | 1.5 | 3.9 | 12.0 | 32.6 | 88.1 | 208.5
Peptic ulcer(K25–K28) | 1.2 | * | * | * | * | 0.1 | 0.3 | 0.7 | 1.5 | 2.9 | 6.1 | 15.0
Diseases of appendix(K35–K38) | 0.1 | * | * | * | * | * | 0.0 | 0.1 | 0.2 | 0.3 | 0.7 | 1.9
Hernia(K40–K46) | 0.8 | * | * | * | * | * | 0.1 | 0.3 | 0.8 | 1.6 | 4.0 | 14.7
Chronic liver disease and cirrhosis(K70,K73–K74) | 16.4 | * | * | * | 0.1 | 3.9 | 12.6 | 23.3 | 39.2 | 39.0 | 36.7 | 30.2
Alcoholic liver disease(K70) | 9.3 | * | * | * | 0.1 | 3.3 | 9.9 | 16.5 | 24.6 | 17.8 | 9.6 | 4.2
Other chronic liver disease and cirrhosis(K73–K74) | 7.2 | * | * | * | * | 0.6 | 2.7 | 6.7 | 14.5 | 21.2 | 27.1 | 26.0
Cholelithiasis and other disorders of gallbladder(K80–K82) | 1.3 | * | * | * | * | 0.0 | 0.1 | 0.3 | 0.9 | 2.7 | 7.8 | 24.7
Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 17.4 | 1.0 | * | * | 0.1 | 0.8 | 2.4 | 6.6 | 15.8 | 38.3 | 97.0 | 264.2
Acute and rapidly progressive nephritic and nephrotic syndrome(N00–N01,N04) | 0.2 | * | * | * | * | * | * | 0.1 | 0.2 | 0.4 | 1.5 | 4.4
Chronic glomerulonephritis, nephritis and nephropathy not specified as acute or chronic, and renal sclerosis unspecified(N02–N03,N05–N07,N26) | 0.1 | * | * | * | * | * | 0.0 | 0.1 | 0.1 | 0.3 | 0.4 | 0.7
Renal failure(N17–N19) | 17.0 | 1.0 | * | * | 0.1 | 0.7 | 2.3 | 6.5 | 15.5 | 37.6 | 95.1 | 259.0
Other disorders of kidney(N25,N27) | 0.0 | * | * | * | * | * | * | * | * | * | * | *
Infections of kidney(N10–N12,N13.6,N15.1) | 0.4 | * | * | * | * | * | 0.1 | 0.2 | 0.3 | 0.8 | 2.0 | 4.3
Hyperplasia of prostate(N40) | 0.3 | * | * | * | * | * | * | * | 0.1 | 0.3 | 1.4 | 6.9
Inflammatory diseases of female pelvic organs(N70–N76) | 0.1 | * | * | * | * | * | * | * | 0.1 | 0.1 | 0.3 | 0.7
Pregnancy, childbirth and the puerperium(O00–O99) | 0.4 | … | … | * | 0.4 | 1.3 | 1.1 | * | * | * | * | *
Pregnancy with abortive outcome(O00–O07) | 0.0 | … | … | * | * | * | * | * | * | * | * | *
Other complications of pregnancy, childbirth and the puerperium(O10–O99) | 0.4 | … | … | * | 0.4 | 1.3 | 1.1 | * | * | * | * | *
Certain conditions originating in the perinatal period(P00–P96) | 3.1 | 273.4 | 0.4 | 0.1 | * | * | * | * | * | * | * | *
Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 3.0 | 107.8 | 3.0 | 1.1 | 0.9 | 1.1 | 1.2 | 1.9 | 3.1 | 2.5 | 3.2 | 5.5
Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified(R00–R99) | 10.2 | 73.1 | 2.1 | 0.3 | 1.3 | 2.9 | 3.9 | 5.2 | 8.6 | 14.8 | 34.3 | 163.2
All other diseases(residual) | 123.3 | 15.3 | 2.8 | 2.0 | 4.5 | 12.5 | 24.8 | 46.9 | 96.9 | 201.4 | 589.5 | 2,460.9
Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 68.1 | 36.8 | 8.7 | 4.0 | 33.1 | 72.7 | 84.6 | 77.6 | 80.8 | 68.5 | 127.8 | 417.4
Transport accidents(V01–V99,Y85) | 14.8 | 2.2 | 2.6 | 2.3 | 16.3 | 19.3 | 17.4 | 16.2 | 17.3 | 16.2 | 19.6 | 22.1
Motor vehicle accidents(V02–V04,V09.0,V09.2,V12–V14,V19.0–V19.2,V19.4–V19.6,V20–V79,V80.3–V80.5,V81.0–V81.1,V82.0–V82.1,V83–V86,V87.0–V87.8,V88.0–V88.8, V89.0,V89.2) | 13.8 | 2.1 | 2.5 | 2.2 | 15.8 | 18.5 | 16.2 | 15.0 | 15.6 | 14.6 | 18.4 | 21.2
Other land transport accidents(V01,V05–V06,V09.1,V09.3–V09.9,V10–V11,V15–V18,V19.3,V19.8–V19.9,V80.0–V80.2,V80.6–V80.9,V81.2–V81.9,V82.2–V82.9,V87.9, V88.9,V89.1,V89.3,V89.9) | 0.4 | * | * | * | 0.2 | 0.4 | 0.5 | 0.4 | 0.6 | 0.5 | 0.4 | 0.3
Water, air and space, and other and unspecified transport accidents and their sequelae(V90–V99,Y85) | 0.6 | * | * | 0.1 | 0.3 | 0.5 | 0.7 | 0.8 | 1.1 | 1.1 | 0.8 | 0.5
Nontransport accidents(W00–X59,Y86) | 53.4 | 34.6 | 6.1 | 1.7 | 16.8 | 53.3 | 67.3 | 61.5 | 63.5 | 52.3 | 108.2 | 395.4
Falls(W00–W19) | 14.0 | * | 0.1 | 0.1 | 0.3 | 0.8 | 1.6 | 3.0 | 7.7 | 19.8 | 76.5 | 321.1
Accidental discharge of firearms(W32–W34) | 0.1 | * | 0.3 | 0.1 | 0.3 | 0.2 | 0.1 | 0.1 | 0.1 | 0.1 | * | *
Accidental drowning and submersion(W65–W74) | 1.3 | 1.1 | 3.1 | 0.5 | 1.0 | 1.1 | 1.1 | 1.0 | 1.3 | 1.6 | 1.8 | 2.1
Accidental exposure to smoke, fire and flames(X00–X09) | 1.0 | * | 0.6 | 0.4 | 0.3 | 0.4 | 0.5 | 0.8 | 1.6 | 2.6 | 3.2 | 4.1
Accidental poisoning and exposure to noxious substances(X40–X49) | 30.9 | 0.8 | 0.5 | 0.2 | 14.0 | 49.0 | 61.3 | 52.8 | 45.9 | 17.5 | 4.0 | 2.5
Other and unspecified nontransport accidents and their sequelae(W20–W31,W35–W64,W75–W99,X10–X39,X50–X59,Y86) | 6.1 | 32.2 | 1.4 | 0.4 | 0.9 | 1.8 | 2.6 | 3.7 | 6.8 | 10.7 | 22.7 | 65.6
Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 14.8 | … | … | 1.2 | 13.6 | 19.0 | 18.7 | 19.2 | 18.7 | 16.0 | 20.3 | 23.0
Intentional self-harm (suicide) by discharge of firearms(X72–X74) | 8.1 | … | … | 0.4 | 7.3 | 9.3 | 8.6 | 9.5 | 10.5 | 10.5 | 15.3 | 17.7
Intentional self-harm (suicide) by other and unspecified means and their sequelae(*U03,X60–X71,X75–X84,Y87.0) | 6.7 | … | … | 0.8 | 6.3 | 9.7 | 10.1 | 9.8 | 8.2 | 5.5 | 4.9 | 5.4
Assault (homicide)(*U01–^*^U02,X85–Y09,Y87.1) | 7.5 | 6.8 | 2.3 | 1.3 | 14.1 | 14.8 | 10.9 | 6.8 | 4.3 | 2.6 | 2.3 | 2.0
Assault (homicide) by discharge of firearms(*U01.4,X93–X95) | 5.9 | * | 0.5 | 1.0 | 13.1 | 12.8 | 8.8 | 4.8 | 2.6 | 1.2 | 0.9 | 0.6
Assault (homicide) by other and unspecified means and their sequelae(*U01.0–^*^U01.3,^*^U01.5–^*^U01.9,^*^U02,X85–X92,X96–Y09,Y87.1) | 1.6 | 6.4 | 1.8 | 0.4 | 1.0 | 1.9 | 2.1 | 2.0 | 1.8 | 1.3 | 1.3 | 1.3
Legal intervention(Y35,Y89.0) | 0.2 | * | * | * | 0.3 | 0.5 | 0.5 | 0.3 | 0.2 | 0.1 | * | *
Events of undetermined intent(Y10–Y34,Y87.2,Y89.9) | 1.7 | 3.3 | 0.9 | 0.2 | 0.9 | 2.2 | 2.7 | 2.5 | 2.3 | 1.4 | 0.9 | 1.1
Discharge of firearms, undetermined intent(Y22–Y24) | 0.1 | * | * | * | 0.2 | 0.2 | 0.1 | 0.1 | 0.1 | 0.1 | * | *
Other and unspecified events of undetermined intent and their sequelae(Y10–Y21,Y25–Y34,Y87.2,Y89.9) | 1.6 | 3.3 | 0.8 | 0.2 | 0.7 | 2.0 | 2.5 | 2.4 | 2.2 | 1.3 | 0.8 | 1.0
Operations of war and their sequelae(Y36,Y89.1) | * | * | * | * | * | * | * | * | * | * | * | *
Complications of medical and surgical care(Y40–Y84,Y88) | 1.1 | 0.5 | * | 0.1 | 0.1 | 0.2 | 0.3 | 0.7 | 1.6 | 3.0 | 5.2 | 8.5
Enterocolitis due to Clostridium difficile(A04.7)^3^ | 1.3 | * | * | * | * | * | 0.1 | 0.3 | 1.0 | 2.9 | 7.9 | 19.2
COVID-19(U07.1)^3^ | 56.0 | 3.8 | 0.7 | 0.3 | 1.0 | 3.6 | 8.8 | 23.9 | 57.6 | 124.5 | 292.2 | 818.2
Dementia-related causes^3^ | 87.9 | * | * | 0.1 | * | * | 0.1 | 0.9 | 9.4 | 67.4 | 476.2 | 2,809.6
Drug-induced deaths^3^ | 33.6 | 2.0 | 1.2 | 0.4 | 15.3 | 51.8 | 65.1 | 57.3 | 50.7 | 20.7 | 6.3 | 4.7
Drug overdose deaths^3^ | 32.4 | 1.9 | 1.2 | 0.4 | 15.1 | 50.6 | 63.1 | 55.3 | 48.1 | 19.0 | 5.3 | 3.7
Alcohol-induced deaths^3^ | 15.4 | * | * | * | 0.5 | 6.6 | 17.0 | 26.8 | 39.7 | 28.8 | 15.7 | 7.6
Firearm-related injuries^3^ | 14.5 | * | 0.9 | 1.5 | 21.1 | 22.9 | 18.1 | 14.8 | 13.4 | 11.9 | 16.5 | 18.5

0.0 Quantity more than zero but less than 0.05.

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

… Category not applicable.

^1^Data for age not stated included in “all ages” but not distributed among age groups.

^2^Death rates for younger than 1 (based on population estimates) differ from infant mortality rates (based on live births); see Technical Notes.

^3^Included in selected categories above. For list of ICD–10 codes included, see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 9 Number of deaths from 113 selected causes, Enterocolitis due to Clostridium difficile, COVID-19, dementia-related causes, drug-induced causes, alcohol-induced causes, and firearm-related injuries, by Hispanic origin and race and sex: United States, 2022

Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10); see Technical Notes in this report]

Cause of death (based on ICD–10) | Total^1^ | | | Hispanic^2^ | | | Non–Hispanic, single race^3^
Cause of death (based on ICD–10) | Total^1^ | | | Hispanic^2^ | | | American Indian and Alaska Native | | | Asian | | | Black | | | Native Hawaiian or Other Pacific Islander | | | White
Cause of death (based on ICD–10) | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All causes | 3,279,857 | 1,719,250 | 1,560,607 | 275,684 | 155,240 | 120,444 | 23,613 | 12,721 | 10,892 | 89,591 | 46,137 | 43,454 | 411,934 | 219,538 | 192,396 | 4,592 | 2,461 | 2,131 | 2,448,093 | 1,267,526 | 1,180,567
Salmonella infections(A01–A02) | 82 | 49 | 33 | 13 | 10 | 3 | – | – | – | 6 | 5 | 1 | 12 | 6 | 6 | 1 | – | 1 | 50 | 28 | 22
Shigellosis and amebiasis(A03,A06) | 17 | 8 | 9 | 7 | 5 | 2 | – | – | – | – | – | – | 2 | – | 2 | – | – | – | 8 | 3 | 5
Certain other intestinal infections(A04,A07–A09) | 7,380 | 3,030 | 4,350 | 625 | 284 | 341 | 57 | 21 | 36 | 182 | 73 | 109 | 765 | 338 | 427 | 12 | 6 | 6 | 5,674 | 2,273 | 3,401
Tuberculosis(A16–A19) | 565 | 354 | 211 | 101 | 75 | 26 | 13 | 6 | 7 | 147 | 101 | 46 | 94 | 57 | 37 | 3 | 1 | 2 | 206 | 113 | 93
Respiratory tuberculosis(A16) | 391 | 258 | 133 | 72 | 55 | 17 | 10 | 5 | 5 | 118 | 87 | 31 | 63 | 40 | 23 | 3 | 1 | 2 | 124 | 69 | 55
Other tuberculosis(A17–A19) | 174 | 96 | 78 | 29 | 20 | 9 | 3 | 1 | 2 | 29 | 14 | 15 | 31 | 17 | 14 | – | – | – | 82 | 44 | 38
Whooping cough(A37) | 2 | 1 | 1 | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | 2 | 1 | 1
Scarlet fever and erysipelas(A38,A46) | 3 | 1 | 2 | 1 | 1 | – | – | – | – | – | – | – | – | – | – | – | – | – | 2 | – | 2
Meningococcal infection(A39) | 27 | 16 | 11 | 9 | 6 | 3 | – | – | – | 1 | – | 1 | 10 | 4 | 6 | – | – | – | 6 | 5 | 1
Septicemia(A40–A41) | 42,261 | 20,977 | 21,284 | 3,259 | 1,652 | 1,607 | 316 | 148 | 168 | 968 | 508 | 460 | 7,134 | 3,403 | 3,731 | 70 | 34 | 36 | 30,197 | 15,053 | 15,144
Syphilis(A50–A53) | 61 | 37 | 24 | 11 | 10 | 1 | 3 | 2 | 1 | 4 | 3 | 1 | 22 | 9 | 13 | 1 | 1 | – | 18 | 11 | 7
Acute poliomyelitis(A80) | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | –
Arthropod-borne viralencephalitis(A83–A84, A85.2) | 6 | 5 | 1 | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | 6 | 5 | 1
Measles(B05) | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | –
Viral hepatitis(B15–B19) | 3,107 | 1,944 | 1,163 | 485 | 303 | 182 | 53 | 24 | 29 | 191 | 111 | 80 | 417 | 268 | 149 | 12 | 10 | 2 | 1,899 | 1,198 | 701
Human immunodeficiencyvirus (HIV) disease(B20–B24) | 4,941 | 3,802 | 1,139 | 751 | 614 | 137 | 41 | 30 | 11 | 50 | 48 | 2 | 2,401 | 1,674 | 727 | 5 | 3 | 2 | 1,613 | 1,371 | 242
Malaria(B50–B54) | 8 | 7 | 1 | – | – | – | – | – | – | – | – | – | 4 | 3 | 1 | – | – | – | 4 | 4 | –
Other and unspecifiedinfectious and parasitic diseases and their sequelae(A00,A05,A20–A36,A42–A44,A48–A49,A54–A79,A81–A82,A85.0–A85.1,A85.8,A86–B04,B06–B09,B25–B49,B55–B99,U07.1) | 198,029 | 108,820 | 89,209 | 21,584 | 12,533 | 9,051 | 1,815 | 918 | 897 | 5,863 | 3,334 | 2,529 | 23,358 | 11,579 | 11,779 | 307 | 170 | 137 | 143,767 | 79,535 | 64,232
Malignant neoplasms(C00–C97) | 608,371 | 319,336 | 289,035 | 47,021 | 24,146 | 22,875 | 3,137 | 1,497 | 1,640 | 19,864 | 10,023 | 9,841 | 70,698 | 35,442 | 35,256 | 849 | 400 | 449 | 462,834 | 245,676 | 217,158
neoplasms(C00–C97) | 608,371 | 319,336 | 289,035 | 47,021 | 24,146 | 22,875 | 3,137 | 1,497 | 1,640 | 19,864 | 10,023 | 9,841 | 70,698 | 35,442 | 35,256 | 849 | 400 | 449 | 462,834 | 245,676 | 217,158
neoplasms(C00–C97) | 608,371 | 319,336 | 289,035 | 47,021 | 24,146 | 22,875 | 3,137 | 1,497 | 1,640 | 19,864 | 10,023 | 9,841 | 70,698 | 35,442 | 35,256 | 849 | 400 | 449 | 462,834 | 245,676 | 217,158
Malignant neoplasms of lip, oral cavity and pharynx(C00–C14) | 11,884 | 8,434 | 3,450 | 706 | 510 | 196 | 67 | 41 | 26 | 489 | 336 | 153 | 1,171 | 853 | 318 | 26 | 18 | 8 | 9,324 | 6,593 | 2,731
Malignant neoplasm of esophagus(C15) | 16,016 | 12,699 | 3,317 | 848 | 676 | 172 | 73 | 53 | 20 | 351 | 272 | 79 | 1,200 | 842 | 358 | 18 | 16 | 2 | 13,424 | 10,760 | 2,664
Malignant neoplasm of stomach(C16) | 10,853 | 6,437 | 4,416 | 2,061 | 1,148 | 913 | 86 | 45 | 41 | 864 | 503 | 361 | 1,863 | 1,067 | 796 | 25 | 16 | 9 | 5,877 | 3,607 | 2,270
Malignant neoplasms of colon, rectum and anus(C18–C21) | 54,268 | 29,029 | 25,239 | 4,958 | 2,778 | 2,180 | 345 | 186 | 159 | 2,011 | 1,096 | 915 | 7,025 | 3,723 | 3,302 | 77 | 41 | 36 | 39,487 | 21,000 | 18,487
Malignant neoplasms of liver and intrahepatic bile ducts(C22) | 28,937 | 18,884 | 10,053 | 4,047 | 2,580 | 1,467 | 234 | 126 | 108 | 1,667 | 1,070 | 597 | 3,535 | 2,376 | 1,159 | 67 | 47 | 20 | 19,152 | 12,512 | 6,640
Malignant neoplasm of pancreas(C25) | 48,323 | 25,186 | 23,137 | 3,895 | 1,958 | 1,937 | 241 | 102 | 139 | 1,634 | 773 | 861 | 5,867 | 2,841 | 3,026 | 64 | 27 | 37 | 36,314 | 19,310 | 17,004
Malignant neoplasm of larynx(C32) | 3,933 | 3,125 | 808 | 238 | 205 | 33 | 22 | 17 | 5 | 60 | 52 | 8 | 609 | 480 | 129 | – | – | – | 2,980 | 2,356 | 624
Malignant neoplasms of trachea, bronchus and lung(C33–C34) | 131,982 | 69,413 | 62,569 | 5,822 | 3,282 | 2,540 | 672 | 299 | 373 | 3,920 | 2,150 | 1,770 | 14,046 | 7,737 | 6,309 | 167 | 79 | 88 | 106,506 | 55,422 | 51,084
Malignant melanoma of skin(C43) | 8,243 | 5,357 | 2,886 | 270 | 153 | 117 | 12 | 7 | 5 | 63 | 36 | 27 | 125 | 60 | 65 | 1 | – | 1 | 7,731 | 5,075 | 2,656
Malignant neoplasm of breast(C50) | 42,672 | 461 | 42,211 | 3,483 | 27 | 3,456 | 201 | 1 | 200 | 1,429 | 11 | 1,418 | 6,413 | 95 | 6,318 | 67 | 1 | 66 | 30,793 | 321 | 30,472
Malignant neoplasm of cervix uteri(C53) | 4,051 | … | 4,051 | 593 | … | 593 | 30 | … | 30 | 162 | … | 162 | 649 | … | 649 | 20 | … | 20 | 2,567 | … | 2,567
Malignant neoplasms of corpus uteri and uterus, part unspecified(C54–C55) | 12,764 | … | 12,764 | 1,153 | … | 1,153 | 56 | … | 56 | 444 | … | 444 | 2,671 | … | 2,671 | 32 | … | 32 | 8,326 | … | 8,326
Malignant neoplasm of ovary(C56) | 13,214 | … | 13,214 | 1,217 | … | 1,217 | 60 | … | 60 | 533 | … | 533 | 1,312 | … | 1,312 | 21 | … | 21 | 9,991 | … | 9,991
Malignant neoplasm of prostate(C61) | 33,363 | 33,363 | … | 2,475 | 2,475 | … | 133 | 133 | … | 714 | 714 | … | 5,543 | 5,543 | … | 33 | 33 | … | 24,274 | 24,274 | …
Malignant neoplasms of kidney and renal pelvis(C64–C65) | 14,488 | 9,519 | 4,969 | 1,364 | 921 | 443 | 121 | 79 | 42 | 385 | 234 | 151 | 1,422 | 910 | 512 | 16 | 8 | 8 | 11,087 | 7,304 | 3,783
Malignant neoplasm of bladder(C67) | 17,334 | 12,460 | 4,874 | 819 | 586 | 233 | 57 | 35 | 22 | 357 | 252 | 105 | 1,313 | 833 | 480 | 16 | 12 | 4 | 14,693 | 10,688 | 4,005
Malignant neoplasms of meninges, brain and other parts of central nervous system(C70–C72) | 17,937 | 10,082 | 7,855 | 1,503 | 817 | 686 | 60 | 39 | 21 | 483 | 271 | 212 | 1,237 | 651 | 586 | 28 | 11 | 17 | 14,506 | 8,215 | 6,291
Malignant neoplasms of lymphoid, hematopoietic and related tissue(C81–C96) | 56,959 | 32,511 | 24,448 | 4,832 | 2,670 | 2,162 | 203 | 100 | 103 | 1,761 | 999 | 762 | 5,912 | 3,156 | 2,756 | 69 | 37 | 32 | 43,852 | 25,354 | 18,498
Hodgkin disease(C81) | 1,056 | 643 | 413 | 150 | 94 | 56 | 3 | 2 | 1 | 24 | 15 | 9 | 99 | 66 | 33 | – | – | – | 770 | 463 | 307
Non-Hodgkin lymphoma(C82–C85) | 19,794 | 11,300 | 8,494 | 1,753 | 965 | 788 | 65 | 33 | 32 | 740 | 430 | 310 | 1,439 | 823 | 616 | 22 | 10 | 12 | 15,667 | 8,976 | 6,691
Leukemia(C91–C95) | 23,324 | 13,487 | 9,837 | 1,897 | 1,051 | 846 | 72 | 34 | 38 | 676 | 396 | 280 | 2,031 | 1,084 | 947 | 33 | 18 | 15 | 18,476 | 10,820 | 7,656
Multiple myeloma and immunoproliferative neoplasms(C88,C90) | 12,616 | 6,992 | 5,624 | 1,020 | 552 | 468 | 62 | 31 | 31 | 312 | 153 | 159 | 2,325 | 1,174 | 1,151 | 14 | 9 | 5 | 8,810 | 5,028 | 3,782
Other and unspecified malignant neoplasms of lymphoid, hematopoietic and related tissue(C96) | 169 | 89 | 80 | 12 | 8 | 4 | 1 | – | 1 | 9 | 5 | 4 | 18 | 9 | 9 | – | – | – | 129 | 67 | 62
All other and unspecified malignant neoplasms(C17,C23–C24,C26–C31,C37–C41,C44–C49,C51–C52,C57–C60,C62–C63,C66,C68–C69,C73–C80,C97) | 81,150 | 42,376 | 38,774 | 6,737 | 3,360 | 3,377 | 464 | 234 | 230 | 2,537 | 1,254 | 1,283 | 8,785 | 4,275 | 4,510 | 102 | 54 | 48 | 61,950 | 32,885 | 29,065
In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 16,034 | 8,467 | 7,567 | 1,019 | 524 | 495 | 67 | 32 | 35 | 447 | 215 | 232 | 1,541 | 721 | 820 | 19 | 7 | 12 | 12,857 | 6,919 | 5,938
Anemias(D50–D64) | 6,021 | 2,768 | 3,253 | 417 | 198 | 219 | 35 | 15 | 20 | 164 | 78 | 86 | 1,251 | 585 | 666 | 10 | 2 | 8 | 4,107 | 1,872 | 2,235
Diabetes mellitus(E10–E14) | 101,209 | 57,557 | 43,652 | 12,508 | 7,033 | 5,475 | 1,219 | 659 | 560 | 3,709 | 1,982 | 1,727 | 17,954 | 9,371 | 8,583 | 303 | 160 | 143 | 64,701 | 37,886 | 26,815
Nutritional deficiencies(E40–E64) | 21,020 | 7,760 | 13,260 | 1,190 | 468 | 722 | 121 | 44 | 77 | 469 | 168 | 301 | 2,053 | 834 | 1,219 | 13 | 3 | 10 | 17,082 | 6,202 | 10,880
Malnutrition(E40–E46) | 20,552 | 7,555 | 12,997 | 1,161 | 456 | 705 | 114 | 40 | 74 | 464 | 167 | 297 | 2,008 | 816 | 1,192 | 13 | 3 | 10 | 16,703 | 6,032 | 10,671
Other nutritional deficiencies(E50–E64) | 468 | 205 | 263 | 29 | 12 | 17 | 7 | 4 | 3 | 5 | 1 | 4 | 45 | 18 | 27 | – | – | – | 379 | 170 | 209
Meningitis(G00,G03) | 604 | 348 | 256 | 77 | 47 | 30 | 5 | 3 | 2 | 25 | 21 | 4 | 130 | 74 | 56 | 2 | – | 2 | 359 | 199 | 160
Parkinson disease(G20–G21) | 39,915 | 24,503 | 15,412 | 2,508 | 1,430 | 1,078 | 113 | 63 | 50 | 1,232 | 742 | 490 | 1,919 | 1,093 | 826 | 19 | 13 | 6 | 33,969 | 21,065 | 12,904
Alzheimer disease(G30) | 120,122 | 37,475 | 82,647 | 9,552 | 2,904 | 6,648 | 337 | 110 | 227 | 3,448 | 1,069 | 2,379 | 9,284 | 2,749 | 6,535 | 98 | 28 | 70 | 96,899 | 30,434 | 66,465
Major cardiovascular diseases(I00–I78) | 936,436 | 492,088 | 444,348 | 67,463 | 36,990 | 30,473 | 4,838 | 2,629 | 2,209 | 27,175 | 14,066 | 13,109 | 122,434 | 64,109 | 58,325 | 1,418 | 776 | 642 | 706,141 | 369,268 | 336,873
Diseases of heart(I00–I09,I11,I13,I20–I51) | 702,880 | 386,766 | 316,114 | 47,715 | 27,442 | 20,273 | 3,753 | 2,152 | 1,601 | 18,091 | 9,980 | 8,111 | 88,964 | 48,430 | 40,534 | 1,004 | 575 | 429 | 537,969 | 294,757 | 243,212
Acute rheumatic fever and chronic rheumatic heart diseases(I00–I09) | 4,294 | 1,522 | 2,772 | 279 | 112 | 167 | 31 | 15 | 16 | 147 | 55 | 92 | 365 | 125 | 240 | 15 | 6 | 9 | 3,423 | 1,196 | 2,227
Hypertensive heart disease(I11) | 72,070 | 36,143 | 35,927 | 5,020 | 2,738 | 2,282 | 502 | 278 | 224 | 1,728 | 820 | 908 | 12,084 | 6,633 | 5,451 | 91 | 54 | 37 | 51,974 | 25,215 | 26,759
Hypertensive heart and renal disease(I13) | 16,091 | 7,521 | 8,570 | 1,000 | 492 | 508 | 140 | 66 | 74 | 376 | 173 | 203 | 2,555 | 1,282 | 1,273 | 23 | 9 | 14 | 11,873 | 5,420 | 6,453
Ischemic heart diseases(I20–I25) | 371,506 | 223,952 | 147,554 | 27,594 | 16,840 | 10,754 | 1,973 | 1,211 | 762 | 10,956 | 6,538 | 4,418 | 43,103 | 24,839 | 18,264 | 551 | 335 | 216 | 284,345 | 172,181 | 112,164
Acute myocardial infarction(I21–I22) | 103,905 | 62,571 | 41,334 | 7,805 | 4,664 | 3,141 | 572 | 346 | 226 | 3,133 | 1,855 | 1,278 | 11,888 | 6,695 | 5,193 | 164 | 90 | 74 | 79,750 | 48,545 | 31,205
Other acute ischemic heart diseases(I24) | 4,823 | 2,756 | 2,067 | 257 | 165 | 92 | 35 | 20 | 15 | 111 | 66 | 45 | 785 | 477 | 308 | 4 | 3 | 1 | 3,594 | 2,003 | 1,591
Other forms of chronic ischemic heart disease(I20,I25) | 262,778 | 158,625 | 104,153 | 19,532 | 12,011 | 7,521 | 1,366 | 845 | 521 | 7,712 | 4,617 | 3,095 | 30,430 | 17,667 | 12,763 | 383 | 242 | 141 | 201,001 | 121,633 | 79,368
Atherosclerotic cardiovascular disease, so described(I25.0) | 81,672 | 52,180 | 29,492 | 7,027 | 4,794 | 2,233 | 540 | 340 | 200 | 2,336 | 1,468 | 868 | 12,755 | 8,093 | 4,662 | 118 | 81 | 37 | 57,732 | 36,571 | 21,161
All other forms of chronic ischemic heart disease(I20,I25.1–I25.9) | 181,106 | 106,445 | 74,661 | 12,505 | 7,217 | 5,288 | 826 | 505 | 321 | 5,376 | 3,149 | 2,227 | 17,675 | 9,574 | 8,101 | 265 | 161 | 104 | 143,269 | 85,062 | 58,207
Other heart diseases(I26–I51) | 238,919 | 117,628 | 121,291 | 13,822 | 7,260 | 6,562 | 1,107 | 582 | 525 | 4,884 | 2,394 | 2,490 | 30,857 | 15,551 | 15,306 | 324 | 171 | 153 | 186,354 | 90,745 | 95,609
Acute and subacute endocarditis(I33) | 1,803 | 1,098 | 705 | 162 | 100 | 62 | 19 | 8 | 11 | 35 | 25 | 10 | 260 | 159 | 101 | 3 | 2 | 1 | 1,308 | 793 | 515
Diseases of pericardium and acute myocarditis(I30–I31,I40) | 1,237 | 634 | 603 | 125 | 64 | 61 | 12 | 4 | 8 | 36 | 25 | 11 | 204 | 93 | 111 | 2 | 1 | 1 | 847 | 439 | 408
Heart failure(I50) | 87,941 | 41,657 | 46,284 | 4,912 | 2,434 | 2,478 | 354 | 187 | 167 | 1,718 | 835 | 883 | 10,476 | 5,101 | 5,375 | 94 | 52 | 42 | 69,972 | 32,820 | 37,152
All other forms of heart disease(I26–I28,I34–I38,I42–I49,I51) | 147,938 | 74,239 | 73,699 | 8,623 | 4,662 | 3,961 | 722 | 383 | 339 | 3,095 | 1,509 | 1,586 | 19,917 | 10,198 | 9,719 | 225 | 116 | 109 | 114,227 | 56,693 | 57,534
Essential hypertension and hypertensive renal disease(I10,I12,I15) | 43,293 | 20,237 | 23,056 | 3,806 | 1,902 | 1,904 | 219 | 102 | 117 | 1,903 | 868 | 1,035 | 7,673 | 3,750 | 3,923 | 68 | 37 | 31 | 29,296 | 13,393 | 15,903
Cerebrovascular diseases(I60–I69) | 165,393 | 71,819 | 93,574 | 14,224 | 6,673 | 7,551 | 747 | 308 | 439 | 6,482 | 2,852 | 3,630 | 22,656 | 10,293 | 12,363 | 298 | 137 | 161 | 119,929 | 51,042 | 68,887
Atherosclerosis(I70) | 3,936 | 1,889 | 2,047 | 288 | 144 | 144 | 13 | 9 | 4 | 132 | 54 | 78 | 373 | 186 | 187 | 4 | 2 | 2 | 3,095 | 1,477 | 1,618
Other diseases of circulatory system (I71–I78) | 20,934 | 11,377 | 9,557 | 1,430 | 829 | 601 | 106 | 58 | 48 | 567 | 312 | 255 | 2,768 | 1,450 | 1,318 | 44 | 25 | 19 | 15,852 | 8,599 | 7,253
Aortic aneurysm and dissection(I71) | 9,999 | 5,962 | 4,037 | 597 | 411 | 186 | 37 | 22 | 15 | 343 | 206 | 137 | 1,146 | 661 | 485 | 26 | 15 | 11 | 7,757 | 4,584 | 3,173
Other diseases of arteries, arterioles and capillaries(I72–I78) | 10,935 | 5,415 | 5,520 | 833 | 418 | 415 | 69 | 36 | 33 | 224 | 106 | 118 | 1,622 | 789 | 833 | 18 | 10 | 8 | 8,095 | 4,015 | 4,080
Other disorders of circulatory system(I80–I99) | 5,216 | 2,652 | 2,564 | 470 | 267 | 203 | 36 | 21 | 15 | 81 | 40 | 41 | 1,032 | 497 | 535 | 3 | 2 | 1 | 3,533 | 1,796 | 1,737
Influenza and pneumonia(J09–J18) | 47,052 | 24,060 | 22,992 | 4,166 | 2,177 | 1,989 | 392 | 198 | 194 | 1,766 | 908 | 858 | 5,335 | 2,772 | 2,563 | 63 | 26 | 37 | 34,951 | 17,775 | 17,176
Influenza(J09–J11) | 5,944 | 2,717 | 3,227 | 580 | 271 | 309 | 74 | 37 | 37 | 139 | 58 | 81 | 546 | 256 | 290 | 18 | 6 | 12 | 4,546 | 2,064 | 2,482
Pneumonia(J12–J18) | 41,108 | 21,343 | 19,765 | 3,586 | 1,906 | 1,680 | 318 | 161 | 157 | 1,627 | 850 | 777 | 4,789 | 2,516 | 2,273 | 45 | 20 | 25 | 30,405 | 15,711 | 14,694
Other acute lower respiratory infections(J20–J22,U04) | 278 | 128 | 150 | 34 | 18 | 16 | 2 | 1 | 1 | 9 | 5 | 4 | 38 | 21 | 17 | 1 | 1 | – | 191 | 80 | 111
Acute bronchitis and bronchiolitis(J20–J21) | 182 | 89 | 93 | 27 | 15 | 12 | 1 | 1 | – | 7 | 5 | 2 | 32 | 18 | 14 | – | – | – | 114 | 49 | 65
Other and unspecified acute lower respiratory infections(J22,U04) | 96 | 39 | 57 | 7 | 3 | 4 | 1 | – | 1 | 2 | – | 2 | 6 | 3 | 3 | 1 | 1 | – | 77 | 31 | 46
Chronic lower respiratory diseases(J40–J47) | 147,382 | 69,004 | 78,378 | 5,615 | 2,796 | 2,819 | 761 | 347 | 414 | 1,785 | 1,058 | 727 | 10,990 | 5,454 | 5,536 | 109 | 58 | 51 | 127,003 | 58,720 | 68,283
Bronchitis, chronic and unspecified(J40–J42) | 358 | 139 | 219 | 20 | 8 | 12 | 3 | 1 | 2 | 12 | 4 | 8 | 33 | 10 | 23 | – | – | – | 288 | 115 | 173
Emphysema(J43) | 7,905 | 4,165 | 3,740 | 253 | 155 | 98 | 44 | 23 | 21 | 134 | 96 | 38 | 514 | 298 | 216 | 5 | 4 | 1 | 6,888 | 3,547 | 3,341
Asthma(J45–J46) | 3,602 | 1,415 | 2,187 | 383 | 162 | 221 | 35 | 12 | 23 | 121 | 53 | 68 | 1,012 | 472 | 540 | 9 | 4 | 5 | 1,972 | 684 | 1,288
Other chronic lower respiratory diseases(J44,J47) | 135,517 | 63,285 | 72,232 | 4,959 | 2,471 | 2,488 | 679 | 311 | 368 | 1,518 | 905 | 613 | 9,431 | 4,674 | 4,757 | 95 | 50 | 45 | 117,855 | 54,374 | 63,481
Pneumoconioses and chemical effects(J60–J66,J68,U07.0) | 562 | 521 | 41 | 20 | 19 | 1 | 7 | 7 | – | 2 | 2 | – | 17 | 14 | 3 | – | – | – | 512 | 475 | 37
Pneumonitis due to solids and liquids(J69) | 20,052 | 11,751 | 8,301 | 1,342 | 733 | 609 | 91 | 49 | 42 | 700 | 395 | 305 | 2,322 | 1,314 | 1,008 | 18 | 13 | 5 | 15,435 | 9,153 | 6,282
Other diseases of respiratory system(J00–J06,J30–J39,J67,J70–J98) | 48,082 | 24,822 | 23,260 | 4,049 | 2,110 | 1,939 | 299 | 148 | 151 | 1,323 | 694 | 629 | 4,746 | 2,307 | 2,439 | 36 | 19 | 17 | 37,344 | 19,384 | 17,960
Peptic ulcer(K25–K28) | 4,105 | 2,191 | 1,914 | 358 | 211 | 147 | 32 | 17 | 15 | 163 | 82 | 81 | 431 | 255 | 176 | 5 | 3 | 2 | 3,079 | 1,597 | 1,482
Diseases of appendix(K35–K38) | 487 | 267 | 220 | 46 | 31 | 15 | 4 | 3 | 1 | 15 | 5 | 10 | 81 | 50 | 31 | 1 | 1 | – | 337 | 175 | 162
Hernia(K40–K46) | 2,712 | 1,223 | 1,489 | 245 | 114 | 131 | 24 | 9 | 15 | 41 | 18 | 23 | 209 | 108 | 101 | 1 | 1 | – | 2,172 | 960 | 1,212
Chronic liver disease and cirrhosis(K70,K73–K74) | 54,803 | 34,340 | 20,463 | 8,933 | 6,067 | 2,866 | 1,579 | 851 | 728 | 910 | 585 | 325 | 4,017 | 2,454 | 1,563 | 46 | 31 | 15 | 38,779 | 24,008 | 14,771
Alcoholic liver disease(K70) | 30,910 | 21,059 | 9,851 | 5,126 | 4,018 | 1,108 | 1,202 | 685 | 517 | 415 | 314 | 101 | 2,218 | 1,423 | 795 | 26 | 20 | 6 | 21,553 | 14,357 | 7,196
Other chronic liver disease and cirrhosis(K73–K74) | 23,893 | 13,281 | 10,612 | 3,807 | 2,049 | 1,758 | 377 | 166 | 211 | 495 | 271 | 224 | 1,799 | 1,031 | 768 | 20 | 11 | 9 | 17,226 | 9,651 | 7,575
Cholelithiasis and other disorders of gallbladder(K80–K82) | 4,483 | 2,287 | 2,196 | 475 | 252 | 223 | 43 | 19 | 24 | 163 | 79 | 84 | 449 | 191 | 258 | 6 | 2 | 4 | 3,326 | 1,730 | 1,596
Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 57,937 | 30,178 | 27,759 | 5,299 | 2,808 | 2,491 | 434 | 227 | 207 | 1,985 | 1,041 | 944 | 10,921 | 5,349 | 5,572 | 121 | 60 | 61 | 38,813 | 20,470 | 18,343
Acute and rapidly progressive nephritic and nephrotic syndrome(N00–N01,N04) | 810 | 429 | 381 | 65 | 34 | 31 | 4 | 2 | 2 | 28 | 19 | 9 | 126 | 63 | 63 | 2 | 1 | 1 | 581 | 307 | 274
Chronic glomerulonephritis, nephritis and nephropathy not specified as acute or chronic, and renal sclerosis unspecified(N02–N03,N05–N07,N26) | 330 | 196 | 134 | 20 | 10 | 10 | 5 | 4 | 1 | 24 | 18 | 6 | 44 | 17 | 27 | 1 | – | 1 | 229 | 142 | 87
Renal failure(N17–N19) | 56,756 | 29,532 | 27,224 | 5,212 | 2,764 | 2,448 | 424 | 221 | 203 | 1,933 | 1,004 | 929 | 10,744 | 5,266 | 5,478 | 118 | 59 | 59 | 37,972 | 20,003 | 17,969
Other disorders of kidney(N25,N27) | 41 | 21 | 20 | 2 | – | 2 | 1 | – | 1 | – | – | – | 7 | 3 | 4 | – | – | – | 31 | 18 | 13
Infections of kidney(N10–N12,N13.6,N15.1) | 1,205 | 437 | 768 | 129 | 39 | 90 | 14 | 5 | 9 | 20 | 6 | 14 | 115 | 50 | 65 | 1 | – | 1 | 918 | 334 | 584
Hyperplasia of prostate(N40) | 839 | 839 | … | 75 | 75 | … | 3 | 3 | … | 25 | 25 | … | 73 | 73 | … | – | – | … | 659 | 659 | …
Inflammatory diseases of female pelvic organs(N70–N76) | 232 | … | 232 | 29 | … | 29 | 3 | … | 3 | 10 | … | 10 | 40 | … | 40 | – | … | – | 148 | … | 148
Pregnancy, childbirth and the puerperium(O00–O99) | 1,263 | … | 1,263 | 227 | … | 227 | 26 | … | 26 | 46 | … | 46 | 395 | … | 395 | 5 | … | 5 | 551 | … | 551
Pregnancy with abortive outcome(O00–O07) | 33 | … | 33 | 7 | … | 7 | 2 | … | 2 | 1 | … | 1 | 11 | … | 11 | 1 | … | 1 | 11 | … | 11
Other complications of pregnancy, childbirth and the puerperium(O10–O99) | 1,230 | … | 1,230 | 220 | … | 220 | 24 | … | 24 | 45 | … | 45 | 384 | … | 384 | 4 | … | 4 | 540 | … | 540
Certain conditions originating in the perinatal period(P00–P96) | 10,203 | 5,695 | 4,508 | 2,402 | 1,346 | 1,056 | 82 | 48 | 34 | 365 | 207 | 158 | 2,976 | 1,687 | 1,289 | 41 | 22 | 19 | 3,826 | 2,098 | 1,728
Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 10,149 | 5,276 | 4,873 | 1,865 | 959 | 906 | 82 | 42 | 40 | 251 | 137 | 114 | 1,530 | 797 | 733 | 24 | 8 | 16 | 6,147 | 3,208 | 2,939
Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified(R00–R99) | 34,110 | 17,133 | 16,977 | 2,954 | 1,810 | 1,144 | 307 | 197 | 110 | 762 | 383 | 379 | 5,299 | 2,865 | 2,434 | 49 | 26 | 23 | 24,235 | 11,538 | 12,697
All other diseases(residual) | 410,973 | 179,851 | 231,122 | 28,956 | 13,645 | 15,311 | 2,873 | 1,363 | 1,510 | 9,208 | 3,911 | 5,297 | 45,588 | 20,363 | 25,225 | 440 | 215 | 225 | 321,231 | 138,958 | 182,273
Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 227,039 | 151,629 | 75,410 | 28,699 | 21,954 | 6,745 | 3,146 | 2,071 | 1,075 | 4,046 | 2,658 | 1,388 | 34,644 | 24,776 | 9,868 | 314 | 227 | 87 | 152,647 | 97,463 | 55,184
Transport accidents(V01–V99,Y85) | 49,178 | 35,769 | 13,409 | 8,871 | 6,689 | 2,182 | 892 | 602 | 290 | 1,054 | 694 | 360 | 8,214 | 5,996 | 2,218 | 95 | 72 | 23 | 29,383 | 21,247 | 8,136
Motor vehicle accidents(V02–V04,V09.0,V09.2,V12–V14,V19.0–V19.2,V19.4–V19.6,V20–V79,V80.3–V80.5,V81.0–V81.1,V82.0–V82.1,V83–V86,V87.0–V87.8,V88.0–V88.8, V89.0,V89.2) | 46,027 | 33,274 | 12,753 | 8,424 | 6,330 | 2,094 | 844 | 569 | 275 | 979 | 632 | 347 | 7,822 | 5,671 | 2,151 | 88 | 68 | 20 | 27,241 | 19,565 | 7,676
Other land transport accidents(V01,V05–V06,V09.1,V09.3–V09.9,V10–V11,V15–V18,V19.3,V19.8–V19.9,V80.0–V80.2,V80.6–V80.9,V81.2–V81.9,V82.2–V82.9,V87.9, V88.9,V89.1,V89.3,V89.9) | 1,195 | 951 | 244 | 245 | 202 | 43 | 24 | 16 | 8 | 34 | 29 | 5 | 169 | 144 | 25 | 2 | 1 | 1 | 703 | 547 | 156
Water, air and space, and other and unspecified transport accidents and their sequelae(V90–V99,Y85) | 1,956 | 1,544 | 412 | 202 | 157 | 45 | 24 | 17 | 7 | 41 | 33 | 8 | 223 | 181 | 42 | 5 | 3 | 2 | 1,439 | 1,135 | 304
Nontransport accidents(W00–X59,Y86) | 177,861 | 115,860 | 62,001 | 19,828 | 15,265 | 4,563 | 2,254 | 1,469 | 785 | 2,992 | 1,964 | 1,028 | 26,430 | 18,780 | 7,650 | 219 | 155 | 64 | 123,264 | 76,216 | 47,048
Falls(W00–W19) | 46,630 | 23,819 | 22,811 | 2,884 | 1,757 | 1,127 | 246 | 139 | 107 | 1,348 | 744 | 604 | 2,161 | 1,238 | 923 | 47 | 28 | 19 | 39,679 | 19,755 | 19,924
Accidental discharge of firearms(W32–W34) | 463 | 409 | 54 | 59 | 51 | 8 | 13 | 11 | 2 | 2 | 1 | 1 | 125 | 111 | 14 | 3 | 3 | – | 253 | 225 | 28
Accidental drowning and submersion(W65–W74) | 4,168 | 3,092 | 1,076 | 700 | 572 | 128 | 61 | 40 | 21 | 169 | 123 | 46 | 642 | 502 | 140 | 15 | 12 | 3 | 2,488 | 1,775 | 713
Accidental exposure to smoke, fire and flames(X00–X09) | 3,478 | 2,079 | 1,399 | 241 | 157 | 84 | 35 | 23 | 12 | 52 | 25 | 27 | 676 | 397 | 279 | 1 | – | 1 | 2,428 | 1,445 | 983
Accidental poisoning and exposure to noxious substances(X40–X49) | 102,958 | 73,988 | 28,970 | 14,137 | 11,433 | 2,704 | 1,665 | 1,093 | 572 | 1,002 | 822 | 180 | 19,979 | 14,792 | 5,187 | 117 | 93 | 24 | 63,851 | 44,176 | 19,675
Other and unspecified nontransport accidents and their sequelae(W20–W31,W35–W64,W75–W99,X10–X39,X50–X59,Y86) | 20,164 | 12,473 | 7,691 | 1,807 | 1,295 | 512 | 234 | 163 | 71 | 419 | 249 | 170 | 2,847 | 1,740 | 1,107 | 36 | 19 | 17 | 14,565 | 8,840 | 5,725
Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 49,476 | 39,273 | 10,203 | 5,122 | 4,128 | 994 | 650 | 475 | 175 | 1,459 | 1,025 | 434 | 3,826 | 3,069 | 757 | 95 | 75 | 20 | 37,481 | 29,861 | 7,620
Intentional self-harm (suicide) by discharge of firearms(X72–X74) | 27,032 | 23,538 | 3,494 | 2,074 | 1,847 | 227 | 256 | 222 | 34 | 372 | 326 | 46 | 2,237 | 1,936 | 301 | 24 | 20 | 4 | 21,732 | 18,895 | 2,837
Intentional self-harm (suicide) by other and unspecified means and their sequelae(*U03,X60–X71,X75–X84,Y87.0) | 22,444 | 15,735 | 6,709 | 3,048 | 2,281 | 767 | 394 | 253 | 141 | 1,087 | 699 | 388 | 1,589 | 1,133 | 456 | 71 | 55 | 16 | 15,749 | 10,966 | 4,783
Assault (homicide)(*U01–*U02,X85–Y09,Y87.1) | 24,849 | 19,977 | 4,872 | 4,482 | 3,684 | 798 | 386 | 302 | 84 | 310 | 201 | 109 | 13,236 | 11,352 | 1,884 | 52 | 44 | 8 | 5,980 | 4,097 | 1,883
Assault (homicide) by discharge of firearms(*U01.4,X93–X95) | 19,651 | 16,428 | 3,223 | 3,500 | 2,977 | 523 | 224 | 185 | 39 | 196 | 137 | 59 | 11,575 | 10,127 | 1,448 | 37 | 34 | 3 | 3,830 | 2,735 | 1,095
Assault (homicide) by other and unspecified means and their sequelae(*U01.0–*U01.3,*U01.5–*U01.9,*U02,X85–X92,X96–Y09,Y87.1) | 5,198 | 3,549 | 1,649 | 982 | 707 | 275 | 162 | 117 | 45 | 114 | 64 | 50 | 1,661 | 1,225 | 436 | 15 | 10 | 5 | 2,150 | 1,362 | 788
Legal intervention(Y35,Y89.0) | 810 | 762 | 48 | 191 | 183 | 8 | 33 | 33 | – | 13 | 11 | 2 | 198 | 183 | 15 | 1 | 1 | – | 364 | 342 | 22
Events of undetermined intent(Y10–Y34,Y87.2,Y89.9) | 5,604 | 3,666 | 1,938 | 552 | 404 | 148 | 103 | 70 | 33 | 107 | 72 | 35 | 1,340 | 931 | 409 | 7 | 6 | 1 | 3,390 | 2,122 | 1,268
Discharge of firearms, undetermined intent(Y22–Y24) | 415 | 312 | 103 | 60 | 48 | 12 | 9 | 6 | 3 | 3 | 2 | 1 | 124 | 102 | 22 | – | – | – | 214 | 151 | 63
Other and unspecified events of undetermined intent and their sequelae(Y10–Y21,Y25–Y34,Y87.2,Y89.9) | 5,189 | 3,354 | 1,835 | 492 | 356 | 136 | 94 | 64 | 30 | 104 | 70 | 34 | 1,216 | 829 | 387 | 7 | 6 | 1 | 3,176 | 1,971 | 1,205
Operations of war and their sequelae(Y36,Y89.1) | 7 | 7 | – | 1 | 1 | – | – | – | – | – | – | – | – | – | – | – | – | – | 6 | 6 | –
Complications of medical and surgical care(Y40–Y84,Y88) | 3,726 | 1,928 | 1,798 | 347 | 176 | 171 | 31 | 14 | 17 | 81 | 42 | 39 | 603 | 287 | 316 | 11 | 6 | 5 | 2,634 | 1,396 | 1,238
Enterocolitis due to Clostridium difficile(A04.7)^4^ | 4,231 | 1,808 | 2,423 | 347 | 159 | 188 | 30 | 7 | 23 | 106 | 45 | 61 | 429 | 203 | 226 | 7 | 5 | 2 | 3,277 | 1,372 | 1,905
COVID-19(U07.1)^4^ | 186,552 | 102,660 | 83,892 | 20,499 | 11,923 | 8,576 | 1,690 | 861 | 829 | 5,450 | 3,120 | 2,330 | 21,896 | 10,778 | 11,118 | 285 | 157 | 128 | 135,484 | 75,114 | 60,370
Dementia-related causes^4^ | 292,881 | 97,470 | 195,411 | 19,213 | 6,209 | 13,004 | 897 | 300 | 597 | 7,591 | 2,463 | 5,128 | 23,599 | 7,687 | 15,912 | 202 | 70 | 132 | 240,132 | 80,270 | 159,862
Drug-induced deaths^4^ | 112,109 | 78,614 | 33,495 | 14,573 | 11,563 | 3,010 | 1,641 | 1,040 | 601 | 1,184 | 909 | 275 | 21,455 | 15,749 | 5,706 | 137 | 104 | 33 | 70,734 | 47,595 | 23,139
Drug overdose deaths^4^ | 107,941 | 75,814 | 32,127 | 14,131 | 11,228 | 2,903 | 1,543 | 980 | 563 | 1,142 | 875 | 267 | 20,725 | 15,222 | 5,503 | 125 | 96 | 29 | 67,974 | 45,811 | 22,163
Alcohol-induced deaths^4^ | 51,191 | 36,426 | 14,765 | 7,467 | 6,028 | 1,439 | 1,904 | 1,180 | 724 | 660 | 539 | 121 | 4,339 | 3,025 | 1,314 | 44 | 34 | 10 | 36,099 | 25,139 | 10,960
Firearm-related injuries^4^ | 48,204 | 41,302 | 6,902 | 5,853 | 5,081 | 772 | 530 | 452 | 78 | 583 | 474 | 109 | 14,203 | 12,410 | 1,793 | 65 | 58 | 7 | 26,323 | 22,285 | 4,038

– Quantity zero.

… Category not applicable.

^1^Includes deaths with origin not stated, origin not classifiable, and two or more races reported; see Technical Notes.

^2^Includes people of Hispanic origin of any race; see Technical Notes.

^3^Only one race reported on death certificate; see Technical Notes.

^4^Included in selected categories above. For list of ICD–10 codes included, see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 10 Death rate for 113 selected causes, Enterocolitis due to Clostridium difficile, COVID-19, dementia-related causes, drug-induced causes, alcohol-induced causes, and firearm-related injuries, by Hispanic origin and race and sex: United States, 2022

[Rates are on an annual basis per 100,000 population in specified group; see Technical Notes in this report. Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards. Data for some Hispanic-origin and race categories should be interpreted with caution because of inconsistencies in reporting these items on death certificates and surveys; see Technical Notes. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10); see Technical Notes in this report]

Cause of death (based on ICD–10) | Total^1^ | | | Hispanic^2^ | | | Non-Hispanic, single race^3^
Cause of death (based on ICD–10) | Total^1^ | | | Hispanic^2^ | | | American Indian and Alaska Native | | | Asian | | | Black | | | Native Hawaiian or Other Pacific Islander | | | White
Cause of death (based on ICD–10) | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All causes | 984.1 | 1,040.2 | 928.9 | 433.0 | 481.0 | 383.7 | 975.4 | 1,062.4 | 890.2 | 441.9 | 472.3 | 413.6 | 979.2 | 1,085.4 | 880.8 | 722.1 | 765.3 | 677.9 | 1,247.6 | 1,299.7 | 1,196.1
Salmonella infections(A01–A02) | 0.0 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | 0.0 | 0.0 | 0.0
Shigellosis and amebiasis(A03,A06) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Certain other intestinal infections(A04,A07–A09) | 2.2 | 1.8 | 2.6 | 1.0 | 0.9 | 1.1 | 2.4 | 1.8 | 2.9 | 0.9 | 0.7 | 1.0 | 1.8 | 1.7 | 2.0 | * | * | * | 2.9 | 2.3 | 3.4
Tuberculosis(A16–A19) | 0.2 | 0.2 | 0.1 | 0.2 | 0.2 | 0.1 | * | * | * | 0.7 | 1.0 | 0.4 | 0.2 | 0.3 | 0.2 | * | * | * | 0.1 | 0.1 | 0.1
Respiratory tuberculosis(A16) | 0.1 | 0.2 | 0.1 | 0.1 | 0.2 | * | * | * | * | 0.6 | 0.9 | 0.3 | 0.1 | 0.2 | 0.1 | * | * | * | 0.1 | 0.1 | 0.1
Other tuberculosis(A17–A19) | 0.1 | 0.1 | 0.0 | 0.0 | 0.1 | * | * | * | * | 0.1 | * | * | 0.1 | * | * | * | * | * | 0.0 | 0.0 | 0.0
Whooping cough(A37) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Scarlet fever and erysipelas(A38,A46) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Meningococcal infection(A39) | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Septicemia(A40–A41) | 12.7 | 12.7 | 12.7 | 5.1 | 5.1 | 5.1 | 13.1 | 12.4 | 13.7 | 4.8 | 5.2 | 4.4 | 17.0 | 16.8 | 17.1 | 11.0 | 10.6 | 11.5 | 15.4 | 15.4 | 15.3
Syphilis(A50–A53) | 0.0 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | * | 0.1 | * | * | * | * | * | * | * | *
Acute poliomyelitis(A80) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Arthropod-borne viralencephalitis(A83–A84, A85.2) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Measles(B05) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Viral hepatitis(B15–B19) | 0.9 | 1.2 | 0.7 | 0.8 | 0.9 | 0.6 | 2.2 | 2.0 | 2.4 | 0.9 | 1.1 | 0.8 | 1.0 | 1.3 | 0.7 | * | * | * | 1.0 | 1.2 | 0.7
Human immunodeficiencyvirus (HIV) disease(B20–B24) | 1.5 | 2.3 | 0.7 | 1.2 | 1.9 | 0.4 | 1.7 | 2.5 | * | 0.2 | 0.5 | * | 5.7 | 8.3 | 3.3 | * | * | * | 0.8 | 1.4 | 0.2
Malaria(B50–B54) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Other and unspecifiedinfectious and parasitic diseases and their sequelae(A00,A05,A20–A36,A42–A44,A48–A49,A54–A79,A81–A82,A85.0–A85.1,A85.8,A86–B04,B06–B09,B25–B49,B55–B99,U07.1) | 59.4 | 65.8 | 53.1 | 33.9 | 38.8 | 28.8 | 75.0 | 76.7 | 73.3 | 28.9 | 34.1 | 24.1 | 55.5 | 57.2 | 53.9 | 48.3 | 52.9 | 43.6 | 73.3 | 81.6 | 65.1
Malignant neoplasms(C00–C97) | 182.5 | 193.2 | 172.0 | 73.9 | 74.8 | 72.9 | 129.6 | 125.0 | 134.0 | 98.0 | 102.6 | 93.7 | 168.0 | 175.2 | 161.4 | 133.5 | 124.4 | 142.8 | 235.9 | 251.9 | 220.0
Malignant neoplasms of lip, oral cavity and pharynx(C00–C14) | 3.6 | 5.1 | 2.1 | 1.1 | 1.6 | 0.6 | 2.8 | 3.4 | 2.1 | 2.4 | 3.4 | 1.5 | 2.8 | 4.2 | 1.5 | 4.1 | * | * | 4.8 | 6.8 | 2.8
Malignant neoplasm of esophagus(C15) | 4.8 | 7.7 | 2.0 | 1.3 | 2.1 | 0.5 | 3.0 | 4.4 | 1.6 | 1.7 | 2.8 | 0.8 | 2.9 | 4.2 | 1.6 | * | * | * | 6.8 | 11.0 | 2.7
Malignant neoplasm of stomach(C16) | 3.3 | 3.9 | 2.6 | 3.2 | 3.6 | 2.9 | 3.6 | 3.8 | 3.4 | 4.3 | 5.1 | 3.4 | 4.4 | 5.3 | 3.6 | 3.9 | * | * | 3.0 | 3.7 | 2.3
Malignant neoplasms of colon, rectum and anus(C18–C21) | 16.3 | 17.6 | 15.0 | 7.8 | 8.6 | 6.9 | 14.3 | 15.5 | 13.0 | 9.9 | 11.2 | 8.7 | 16.7 | 18.4 | 15.1 | 12.1 | 12.7 | 11.5 | 20.1 | 21.5 | 18.7
Malignant neoplasms of liver and intrahepatic bile ducts(C22) | 8.7 | 11.4 | 6.0 | 6.4 | 8.0 | 4.7 | 9.7 | 10.5 | 8.8 | 8.2 | 11.0 | 5.7 | 8.4 | 11.7 | 5.3 | 10.5 | 14.6 | 6.4 | 9.8 | 12.8 | 6.7
Malignant neoplasm of pancreas(C25) | 14.5 | 15.2 | 13.8 | 6.1 | 6.1 | 6.2 | 10.0 | 8.5 | 11.4 | 8.1 | 7.9 | 8.2 | 13.9 | 14.0 | 13.9 | 10.1 | 8.4 | 11.8 | 18.5 | 19.8 | 17.2
Malignant neoplasm of larynx(C32) | 1.2 | 1.9 | 0.5 | 0.4 | 0.6 | 0.1 | 0.9 | * | * | 0.3 | 0.5 | * | 1.4 | 2.4 | 0.6 | * | * | * | 1.5 | 2.4 | 0.6
Malignant neoplasms of trachea, bronchus and lung(C33–C34) | 39.6 | 42.0 | 37.2 | 9.1 | 10.2 | 8.1 | 27.8 | 25.0 | 30.5 | 19.3 | 22.0 | 16.8 | 33.4 | 38.3 | 28.9 | 26.3 | 24.6 | 28.0 | 54.3 | 56.8 | 51.8
Malignant melanoma of skin(C43) | 2.5 | 3.2 | 1.7 | 0.4 | 0.5 | 0.4 | * | * | * | 0.3 | 0.4 | 0.3 | 0.3 | 0.3 | 0.3 | * | * | * | 3.9 | 5.2 | 2.7
Malignant neoplasm of breast(C50) | 12.8 | 0.3 | 25.1 | 5.5 | 0.1 | 11.0 | 8.3 | * | 16.3 | 7.0 | * | 13.5 | 15.2 | 0.5 | 28.9 | 10.5 | * | 21.0 | 15.7 | 0.3 | 30.9
Malignant neoplasm of cervix uteri(C53) | 1.2 | … | 2.4 | 0.9 | … | 1.9 | 1.2 | … | 2.5 | 0.8 | … | 1.5 | 1.5 | … | 3.0 | 3.1 | … | 6.4 | 1.3 | … | 2.6
Malignant neoplasms of corpus uteri and uterus, part unspecified(C54–C55) | 3.8 | … | 7.6 | 1.8 | … | 3.7 | 2.3 | … | 4.6 | 2.2 | … | 4.2 | 6.3 | … | 12.2 | 5.0 | … | 10.2 | 4.2 | … | 8.4
Malignant neoplasm of ovary(C56) | 4.0 | … | 7.9 | 1.9 | … | 3.9 | 2.5 | … | 4.9 | 2.6 | … | 5.1 | 3.1 | … | 6.0 | 3.3 | … | 6.7 | 5.1 | … | 10.1
Malignant neoplasm of prostate(C61) | 10.0 | 20.2 | … | 3.9 | 7.7 | … | 5.5 | 11.1 | … | 3.5 | 7.3 | … | 13.2 | 27.4 | … | 5.2 | 10.3 | … | 12.4 | 24.9 | …
Malignant neoplasms of kidney and renal pelvis(C64–C65) | 4.3 | 5.8 | 3.0 | 2.1 | 2.9 | 1.4 | 5.0 | 6.6 | 3.4 | 1.9 | 2.4 | 1.4 | 3.4 | 4.5 | 2.3 | * | * | * | 5.7 | 7.5 | 3.8
Malignant neoplasm of bladder(C67) | 5.2 | 7.5 | 2.9 | 1.3 | 1.8 | 0.7 | 2.4 | 2.9 | 1.8 | 1.8 | 2.6 | 1.0 | 3.1 | 4.1 | 2.2 | * | * | * | 7.5 | 11.0 | 4.1
Malignant neoplasms of meninges, brain and other parts of central nervous system(C70–C72) | 5.4 | 6.1 | 4.7 | 2.4 | 2.5 | 2.2 | 2.5 | 3.3 | 1.7 | 2.4 | 2.8 | 2.0 | 2.9 | 3.2 | 2.7 | 4.4 | * | * | 7.4 | 8.4 | 6.4
Malignant neoplasms of lymphoid, hematopoietic and related tissue(C81–C96) | 17.1 | 19.7 | 14.6 | 7.6 | 8.3 | 6.9 | 8.4 | 8.4 | 8.4 | 8.7 | 10.2 | 7.3 | 14.1 | 15.6 | 12.6 | 10.9 | 11.5 | 10.2 | 22.3 | 26.0 | 18.7
Hodgkin disease(C81) | 0.3 | 0.4 | 0.2 | 0.2 | 0.3 | 0.2 | * | * | * | 0.1 | * | * | 0.2 | 0.3 | 0.2 | * | * | * | 0.4 | 0.5 | 0.3
Non-Hodgkin lymphom(C82–C85) | 5.9 | 6.8 | 5.1 | 2.8 | 3.0 | 2.5 | 2.7 | 2.8 | 2.6 | 3.6 | 4.4 | 3.0 | 3.4 | 4.1 | 2.8 | 3.5 | * | * | 8.0 | 9.2 | 6.8
Leukemia(C91–C95) | 7.0 | 8.2 | 5.9 | 3.0 | 3.3 | 2.7 | 3.0 | 2.8 | 3.1 | 3.3 | 4.1 | 2.7 | 4.8 | 5.4 | 4.3 | 5.2 | * | * | 9.4 | 11.1 | 7.8
Multiple myeloma and immunoproliferative neoplasms(C88,C90) | 3.8 | 4.2 | 3.3 | 1.6 | 1.7 | 1.5 | 2.6 | 2.6 | 2.5 | 1.5 | 1.6 | 1.5 | 5.5 | 5.8 | 5.3 | * | * | * | 4.5 | 5.2 | 3.8
Other and unspecified malignant neoplasms of lymphoid, hematopoietic and related tissue(C96) | 0.1 | 0.1 | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | 0.1 | 0.1 | 0.1
All other and unspecified malignant neoplasms(C17,C23–C24,C26–C31,C37–C41,C44–C49,C51–C52,C57–C60,C62–C63,C66,C68–C69,C73–C80,C97) | 24.3 | 25.6 | 23.1 | 10.6 | 10.4 | 10.8 | 19.2 | 19.5 | 18.8 | 12.5 | 12.8 | 12.2 | 20.9 | 21.1 | 20.6 | 16.0 | 16.8 | 15.3 | 31.6 | 33.7 | 29.4
In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 4.8 | 5.1 | 4.5 | 1.6 | 1.6 | 1.6 | 2.8 | 2.7 | 2.9 | 2.2 | 2.2 | 2.2 | 3.7 | 3.6 | 3.8 | * | * | * | 6.6 | 7.1 | 6.0
Anemias(D50–D64) | 1.8 | 1.7 | 1.9 | 0.7 | 0.6 | 0.7 | 1.4 | * | 1.6 | 0.8 | 0.8 | 0.8 | 3.0 | 2.9 | 3.0 | * | * | * | 2.1 | 1.9 | 2.3
Diabetes mellitus(E10–E14) | 30.4 | 34.8 | 26.0 | 19.6 | 21.8 | 17.4 | 50.4 | 55.0 | 45.8 | 18.3 | 20.3 | 16.4 | 42.7 | 46.3 | 39.3 | 47.6 | 49.8 | 45.5 | 33.0 | 38.8 | 27.2
Nutritional deficiencies(E40–E64) | 6.3 | 4.7 | 7.9 | 1.9 | 1.4 | 2.3 | 5.0 | 3.7 | 6.3 | 2.3 | 1.7 | 2.9 | 4.9 | 4.1 | 5.6 | * | * | * | 8.7 | 6.4 | 11.0
Malnutrition(E40–E46) | 6.2 | 4.6 | 7.7 | 1.8 | 1.4 | 2.2 | 4.7 | 3.3 | 6.0 | 2.3 | 1.7 | 2.8 | 4.8 | 4.0 | 5.5 | * | * | * | 8.5 | 6.2 | 10.8
Other nutritional deficiencies(E50–E64) | 0.1 | 0.1 | 0.2 | 0.0 | * | * | * | * | * | * | * | * | 0.1 | * | 0.1 | * | * | * | 0.2 | 0.2 | 0.2
Meningitis(G00,G03) | 0.2 | 0.2 | 0.2 | 0.1 | 0.1 | 0.1 | * | * | * | 0.1 | 0.2 | * | 0.3 | 0.4 | 0.3 | * | * | * | 0.2 | 0.2 | 0.2
Parkinson disease(G20–G21) | 12.0 | 14.8 | 9.2 | 3.9 | 4.4 | 3.4 | 4.7 | 5.3 | 4.1 | 6.1 | 7.6 | 4.7 | 4.6 | 5.4 | 3.8 | * | * | * | 17.3 | 21.6 | 13.1
Alzheimer disease(G30) | 36.0 | 22.7 | 49.2 | 15.0 | 9.0 | 21.2 | 13.9 | 9.2 | 18.6 | 17.0 | 10.9 | 22.6 | 22.1 | 13.6 | 29.9 | 15.4 | 8.7 | 22.3 | 49.4 | 31.2 | 67.3
Major cardiovascular diseases(I00–I78) | 281.0 | 297.7 | 264.5 | 106.0 | 114.6 | 97.1 | 199.8 | 219.6 | 180.5 | 134.0 | 144.0 | 124.8 | 291.0 | 317.0 | 267.0 | 223.0 | 241.3 | 204.2 | 359.9 | 378.7 | 341.3
Diseases of heart(I00–I09,I11,I13,I20–I51) | 210.9 | 234.0 | 188.2 | 74.9 | 85.0 | 64.6 | 155.0 | 179.7 | 130.8 | 89.2 | 102.2 | 77.2 | 211.5 | 239.4 | 185.6 | 157.9 | 178.8 | 136.5 | 274.2 | 302.2 | 246.4
Acute rheumatic fever and chronic rheumatic heart diseases(I00–I09) | 1.3 | 0.9 | 1.6 | 0.4 | 0.3 | 0.5 | 1.3 | * | * | 0.7 | 0.6 | 0.9 | 0.9 | 0.6 | 1.1 | * | * | * | 1.7 | 1.2 | 2.3
Hypertensive heart disease(I11) | 21.6 | 21.9 | 21.4 | 7.9 | 8.5 | 7.3 | 20.7 | 23.2 | 18.3 | 8.5 | 8.4 | 8.6 | 28.7 | 32.8 | 25.0 | 14.3 | 16.8 | 11.8 | 26.5 | 25.9 | 27.1
Hypertensive heart and renal disease(I13) | 4.8 | 4.6 | 5.1 | 1.6 | 1.5 | 1.6 | 5.8 | 5.5 | 6.0 | 1.9 | 1.8 | 1.9 | 6.1 | 6.3 | 5.8 | 3.6 | * | * | 6.1 | 5.6 | 6.5
Ischemic heart diseases(I20–I25) | 111.5 | 135.5 | 87.8 | 43.3 | 52.2 | 34.3 | 81.5 | 101.1 | 62.3 | 54.0 | 66.9 | 42.0 | 102.5 | 122.8 | 83.6 | 86.6 | 104.2 | 68.7 | 144.9 | 176.6 | 113.6
Acute myocardial infarction(I21–I22) | 31.2 | 37.9 | 24.6 | 12.3 | 14.4 | 10.0 | 23.6 | 28.9 | 18.5 | 15.5 | 19.0 | 12.2 | 28.3 | 33.1 | 23.8 | 25.8 | 28.0 | 23.5 | 40.6 | 49.8 | 31.6
Other acute ischemic heart diseases(I24) | 1.4 | 1.7 | 1.2 | 0.4 | 0.5 | 0.3 | 1.4 | 1.7 | * | 0.5 | 0.7 | 0.4 | 1.9 | 2.4 | 1.4 | * | * | * | 1.8 | 2.1 | 1.6
Other forms of chronic ischemic heart disease(I20,I25) | 78.8 | 96.0 | 62.0 | 30.7 | 37.2 | 24.0 | 56.4 | 70.6 | 42.6 | 38.0 | 47.3 | 29.5 | 72.3 | 87.3 | 58.4 | 60.2 | 75.3 | 44.9 | 102.4 | 124.7 | 80.4
Atherosclerotic cardiovascular disease, so described(I25.0) | 24.5 | 31.6 | 17.6 | 11.0 | 14.9 | 7.1 | 22.3 | 28.4 | 16.3 | 11.5 | 15.0 | 8.3 | 30.3 | 40.0 | 21.3 | 18.6 | 25.2 | 11.8 | 29.4 | 37.5 | 21.4
All other forms of chronic ischemic heart disease(I20,I25.1–I25.9) | 54.3 | 64.4 | 44.4 | 19.6 | 22.4 | 16.8 | 34.1 | 42.2 | 26.2 | 26.5 | 32.2 | 21.2 | 42.0 | 47.3 | 37.1 | 41.7 | 50.1 | 33.1 | 73.0 | 87.2 | 59.0
Other heart diseases(I26–I51) | 71.7 | 71.2 | 72.2 | 21.7 | 22.5 | 20.9 | 45.7 | 48.6 | 42.9 | 24.1 | 24.5 | 23.7 | 73.3 | 76.9 | 70.1 | 50.9 | 53.2 | 48.7 | 95.0 | 93.1 | 96.9
Acute and subacute endocarditis(I33) | 0.5 | 0.7 | 0.4 | 0.3 | 0.3 | 0.2 | * | * | * | 0.2 | 0.3 | * | 0.6 | 0.8 | 0.5 | * | * | * | 0.7 | 0.8 | 0.5
Diseases of pericardium and acute myocarditis(I30–I31,I40) | 0.4 | 0.4 | 0.4 | 0.2 | 0.2 | 0.2 | * | * | * | 0.2 | 0.3 | * | 0.5 | 0.5 | 0.5 | * | * | * | 0.4 | 0.5 | 0.4
Heart failure(I50) | 26.4 | 25.2 | 27.5 | 7.7 | 7.5 | 7.9 | 14.6 | 15.6 | 13.6 | 8.5 | 8.5 | 8.4 | 24.9 | 25.2 | 24.6 | 14.8 | 16.2 | 13.4 | 35.7 | 33.7 | 37.6
All other forms of heart disease(I26–I28,I34–I38,I42–I49,I51) | 44.4 | 44.9 | 43.9 | 13.5 | 14.4 | 12.6 | 29.8 | 32.0 | 27.7 | 15.3 | 15.4 | 15.1 | 47.3 | 50.4 | 44.5 | 35.4 | 36.1 | 34.7 | 58.2 | 58.1 | 58.3
Essential hypertension and hypertensive renal disease(I10,I12,I15) | 13.0 | 12.2 | 13.7 | 6.0 | 5.9 | 6.1 | 9.0 | 8.5 | 9.6 | 9.4 | 8.9 | 9.9 | 18.2 | 18.5 | 18.0 | 10.7 | 11.5 | 9.9 | 14.9 | 13.7 | 16.1
Cerebrovascular diseases(I60–I69) | 49.6 | 43.5 | 55.7 | 22.3 | 20.7 | 24.1 | 30.9 | 25.7 | 35.9 | 32.0 | 29.2 | 34.5 | 53.9 | 50.9 | 56.6 | 46.9 | 42.6 | 51.2 | 61.1 | 52.3 | 69.8
Atherosclerosis(I70) | 1.2 | 1.1 | 1.2 | 0.5 | 0.4 | 0.5 | * | * | * | 0.7 | 0.6 | 0.7 | 0.9 | 0.9 | 0.9 | * | * | * | 1.6 | 1.5 | 1.6
Other diseases of circulatory system (I71–I78) | 6.3 | 6.9 | 5.7 | 2.2 | 2.6 | 1.9 | 4.4 | 4.8 | 3.9 | 2.8 | 3.2 | 2.4 | 6.6 | 7.2 | 6.0 | 6.9 | 7.8 | * | 8.1 | 8.8 | 7.3
Aortic aneurysm and dissection(I71) | 3.0 | 3.6 | 2.4 | 0.9 | 1.3 | 0.6 | 1.5 | 1.8 | * | 1.7 | 2.1 | 1.3 | 2.7 | 3.3 | 2.2 | 4.1 | * | * | 4.0 | 4.7 | 3.2
Other diseases of arteries, arterioles and capillaries(I72–I78) | 3.3 | 3.3 | 3.3 | 1.3 | 1.3 | 1.3 | 2.9 | 3.0 | 2.7 | 1.1 | 1.1 | 1.1 | 3.9 | 3.9 | 3.8 | * | * | * | 4.1 | 4.1 | 4.1
Other disorders of circulatory system(I80–I99) | 1.6 | 1.6 | 1.5 | 0.7 | 0.8 | 0.6 | 1.5 | 1.8 | * | 0.4 | 0.4 | 0.4 | 2.5 | 2.5 | 2.4 | * | * | * | 1.8 | 1.8 | 1.8
Influenza and pneumonia(J09–J18) | 14.1 | 14.6 | 13.7 | 6.5 | 6.7 | 6.3 | 16.2 | 16.5 | 15.9 | 8.7 | 9.3 | 8.2 | 12.7 | 13.7 | 11.7 | 9.9 | 8.1 | 11.8 | 17.8 | 18.2 | 17.4
Influenza(J09–J11) | 1.8 | 1.6 | 1.9 | 0.9 | 0.8 | 1.0 | 3.1 | 3.1 | 3.0 | 0.7 | 0.6 | 0.8 | 1.3 | 1.3 | 1.3 | * | * | * | 2.3 | 2.1 | 2.5
Pneumonia(J12–J18) | 12.3 | 12.9 | 11.8 | 5.6 | 5.9 | 5.4 | 13.1 | 13.4 | 12.8 | 8.0 | 8.7 | 7.4 | 11.4 | 12.4 | 10.4 | 7.1 | 6.2 | 8.0 | 15.5 | 16.1 | 14.9
Other acute lower respiratory infections(J20–J22,U04) | 0.1 | 0.1 | 0.1 | 0.1 | * | * | * | * | * | * | * | * | 0.1 | 0.1 | * | * | * | * | 0.1 | 0.1 | 0.1
Acute bronchitis and bronchiolitis(J20–J21) | 0.1 | 0.1 | 0.1 | 0.0 | * | * | * | * | * | * | * | * | 0.1 | * | * | * | * | * | 0.1 | 0.1 | 0.1
Other and unspecified acute lower respiratory infections(J22,U04) | 0.0 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | 0.0 | 0.0 | 0.0
Chronic lower respiratory diseases(J40–J47) | 44.2 | 41.7 | 46.7 | 8.8 | 8.7 | 9.0 | 31.4 | 29.0 | 33.8 | 8.8 | 10.8 | 6.9 | 26.1 | 27.0 | 25.3 | 17.1 | 18.0 | 16.2 | 64.7 | 60.2 | 69.2
Bronchitis, chronic and unspecified(J40–J42) | 0.1 | 0.1 | 0.1 | 0.0 | * | * | * | * | * | * | * | * | 0.1 | * | 0.1 | * | * | * | 0.1 | 0.1 | 0.2
Emphysema(J43) | 2.4 | 2.5 | 2.2 | 0.4 | 0.5 | 0.3 | 1.8 | 1.9 | 1.7 | 0.7 | 1.0 | 0.4 | 1.2 | 1.5 | 1.0 | * | * | * | 3.5 | 3.6 | 3.4
Asthma(J45–J46) | 1.1 | 0.9 | 1.3 | 0.6 | 0.5 | 0.7 | 1.4 | * | 1.9 | 0.6 | 0.5 | 0.6 | 2.4 | 2.3 | 2.5 | * | * | * | 1.0 | 0.7 | 1.3
Other chronic lower respiratory diseases(J44,J47) | 40.7 | 38.3 | 43.0 | 7.8 | 7.7 | 7.9 | 28.0 | 26.0 | 30.1 | 7.5 | 9.3 | 5.8 | 22.4 | 23.1 | 21.8 | 14.9 | 15.5 | 14.3 | 60.1 | 55.8 | 64.3
Pneumoconioses and chemical effects(J60–J66,J68,U07.0) | 0.2 | 0.3 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | 0.3 | 0.5 | 0.0
Pneumonitis due to solids and liquids(J69) | 6.0 | 7.1 | 4.9 | 2.1 | 2.3 | 1.9 | 3.8 | 4.1 | 3.4 | 3.5 | 4.0 | 2.9 | 5.5 | 6.5 | 4.6 | * | * | * | 7.9 | 9.4 | 6.4
Other diseases of respiratory system(J00–J06,J30–J39,J67,J70–J98) | 14.4 | 15.0 | 13.8 | 6.4 | 6.5 | 6.2 | 12.4 | 12.4 | 12.3 | 6.5 | 7.1 | 6.0 | 11.3 | 11.4 | 11.2 | 5.7 | * | * | 19.0 | 19.9 | 18.2
Peptic ulcer(K25–K28) | 1.2 | 1.3 | 1.1 | 0.6 | 0.7 | 0.5 | 1.3 | * | * | 0.8 | 0.8 | 0.8 | 1.0 | 1.3 | 0.8 | * | * | * | 1.6 | 1.6 | 1.5
Diseases of appendix(K35–K38) | 0.1 | 0.2 | 0.1 | 0.1 | 0.1 | * | * | * | * | * | * | * | 0.2 | 0.2 | 0.1 | * | * | * | 0.2 | 0.2 | 0.2
Hernia(K40–K46) | 0.8 | 0.7 | 0.9 | 0.4 | 0.4 | 0.4 | 1.0 | * | * | 0.2 | * | 0.2 | 0.5 | 0.5 | 0.5 | * | * | * | 1.1 | 1.0 | 1.2
Chronic liver disease and cirrhosis(K70,K73–K74) | 16.4 | 20.8 | 12.2 | 14.0 | 18.8 | 9.1 | 65.2 | 71.1 | 59.5 | 4.5 | 6.0 | 3.1 | 9.5 | 12.1 | 7.2 | 7.2 | 9.6 | * | 19.8 | 24.6 | 15.0
Alcoholic liver disease(K70) | 9.3 | 12.7 | 5.9 | 8.1 | 12.4 | 3.5 | 49.6 | 57.2 | 42.3 | 2.0 | 3.2 | 1.0 | 5.3 | 7.0 | 3.6 | 4.1 | 6.2 | * | 11.0 | 14.7 | 7.3
Other chronic liver disease and cirrhosis(K73–K74) | 7.2 | 8.0 | 6.3 | 6.0 | 6.3 | 5.6 | 15.6 | 13.9 | 17.2 | 2.4 | 2.8 | 2.1 | 4.3 | 5.1 | 3.5 | 3.1 | * | * | 8.8 | 9.9 | 7.7
Cholelithiasis and other disorders of gallbladder(K80–K82) | 1.3 | 1.4 | 1.3 | 0.7 | 0.8 | 0.7 | 1.8 | * | 2.0 | 0.8 | 0.8 | 0.8 | 1.1 | 0.9 | 1.2 | * | * | * | 1.7 | 1.8 | 1.6
Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 17.4 | 18.3 | 16.5 | 8.3 | 8.7 | 7.9 | 17.9 | 19.0 | 16.9 | 9.8 | 10.7 | 9.0 | 26.0 | 26.4 | 25.5 | 19.0 | 18.7 | 19.4 | 19.8 | 21.0 | 18.6
Acute and rapidly progressive nephritic and nephrotic syndrome(N00–N01,N04) | 0.2 | 0.3 | 0.2 | 0.1 | 0.1 | 0.1 | * | * | * | 0.1 | * | * | 0.3 | 0.3 | 0.3 | * | * | * | 0.3 | 0.3 | 0.3
Chronic glomerulonephritis, nephritis and nephropathy not specified as acute or chronic, and renal sclerosis unspecified(N02–N03,N05–N07,N26) | 0.1 | 0.1 | 0.1 | 0.0 | * | * | * | * | * | 0.1 | * | * | 0.1 | * | 0.1 | * | * | * | 0.1 | 0.1 | 0.1
Renal failure(N17–N19) | 17.0 | 17.9 | 16.2 | 8.2 | 8.6 | 7.8 | 17.5 | 18.5 | 16.6 | 9.5 | 10.3 | 8.8 | 25.5 | 26.0 | 25.1 | 18.6 | 18.3 | 18.8 | 19.4 | 20.5 | 18.2
Other disorders of kidney(N25,N27) | 0.0 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | 0.0 | * | *
Infections of kidney(N10–N12,N13.6,N15.1) | 0.4 | 0.3 | 0.5 | 0.2 | 0.1 | 0.3 | * | * | * | 0.1 | * | * | 0.3 | 0.2 | 0.3 | * | * | * | 0.5 | 0.3 | 0.6
Hyperplasia of prostate(N40) | 0.3 | 0.5 | … | 0.1 | 0.2 | … | * | * | … | 0.1 | 0.3 | … | 0.2 | 0.4 | … | * | * | … | 0.3 | 0.7 | …
Inflammatory diseases of female pelvic organs(N70–N76) | 0.1 | … | 0.1 | 0.0 | … | 0.1 | * | … | * | * | … | * | 0.1 | … | 0.2 | * | … | * | 0.1 | … | 0.1
Pregnancy, childbirth and the puerperium(O00–O99) | 0.4 | … | 0.8 | 0.4 | … | 0.7 | 1.1 | … | 2.1 | 0.2 | … | 0.4 | 0.9 | … | 1.8 | * | … | * | 0.3 | … | 0.6
Pregnancy with abortive outcome(O00–O07) | 0.0 | … | 0.0 | * | … | * | * | … | * | * | … | * | * | … | * | * | … | * | * | … | *
Other complications of pregnancy, childbirth and the puerperium(O10–O99) | 0.4 | … | 0.7 | 0.3 | … | 0.7 | 1.0 | … | 2.0 | 0.2 | … | 0.4 | 0.9 | … | 1.8 | * | … | * | 0.3 | … | 0.5
Certain conditions originating in the perinatal period(P00–P96) | 3.1 | 3.4 | 2.7 | 3.8 | 4.2 | 3.4 | 3.4 | 4.0 | 2.8 | 1.8 | 2.1 | 1.5 | 7.1 | 8.3 | 5.9 | 6.4 | 6.8 | * | 1.9 | 2.2 | 1.8
Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 3.0 | 3.2 | 2.9 | 2.9 | 3.0 | 2.9 | 3.4 | 3.5 | 3.3 | 1.2 | 1.4 | 1.1 | 3.6 | 3.9 | 3.4 | 3.8 | * | * | 3.1 | 3.3 | 3.0
Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified(R00–R99) | 10.2 | 10.4 | 10.1 | 4.6 | 5.6 | 3.6 | 12.7 | 16.5 | 9.0 | 3.8 | 3.9 | 3.6 | 12.6 | 14.2 | 11.1 | 7.7 | 8.1 | 7.3 | 12.4 | 11.8 | 12.9
All other diseases(residual) | 123.3 | 108.8 | 137.6 | 45.5 | 42.3 | 48.8 | 118.7 | 113.8 | 123.4 | 45.4 | 40.0 | 50.4 | 108.4 | 100.7 | 115.5 | 69.2 | 66.9 | 71.6 | 163.7 | 142.5 | 184.7
Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 68.1 | 91.7 | 44.9 | 45.1 | 68.0 | 21.5 | 129.9 | 173.0 | 87.9 | 20.0 | 27.2 | 13.2 | 82.3 | 122.5 | 45.2 | 49.4 | 70.6 | 27.7 | 77.8 | 99.9 | 55.9
Transport accidents(V01–V99,Y85) | 14.8 | 21.6 | 8.0 | 13.9 | 20.7 | 7.0 | 36.8 | 50.3 | 23.7 | 5.2 | 7.1 | 3.4 | 19.5 | 29.6 | 10.2 | 14.9 | 22.4 | 7.3 | 15.0 | 21.8 | 8.2
Motor vehicle accidents(V02–V04,V09.0,V09.2,V12–V14,V19.0–V19.2,V19.4–V19.6,V20–V79,V80.3–V80.5,V81.0–V81.1,V82.0–V82.1,V83–V86,V87.0–V87.8,V88.0–V88.8, V89.0,V89.2) | 13.8 | 20.1 | 7.6 | 13.2 | 19.6 | 6.7 | 34.9 | 47.5 | 22.5 | 4.8 | 6.5 | 3.3 | 18.6 | 28.0 | 9.8 | 13.8 | 21.1 | 6.4 | 13.9 | 20.1 | 7.8
Other land transport accidents(V01,V05–V06,V09.1,V09.3–V09.9,V10–V11,V15–V18,V19.3,V19.8–V19.9,V80.0–V80.2,V80.6–V80.9,V81.2–V81.9,V82.2–V82.9,V87.9, V88.9,V89.1,V89.3,V89.9) | 0.4 | 0.6 | 0.1 | 0.4 | 0.6 | 0.1 | 1.0 | * | * | 0.2 | 0.3 | * | 0.4 | 0.7 | 0.1 | * | * | * | 0.4 | 0.6 | 0.2
Water, air and space, and other and unspecified transport accidents and their sequelae(V90–V99,Y85) | 0.6 | 0.9 | 0.2 | 0.3 | 0.5 | 0.1 | 1.0 | * | * | 0.2 | 0.3 | * | 0.5 | 0.9 | 0.2 | * | * | * | 0.7 | 1.2 | 0.3
Nontransport accidents(W00–X59,Y86) | 53.4 | 70.1 | 36.9 | 31.1 | 47.3 | 14.5 | 93.1 | 122.7 | 64.2 | 14.8 | 20.1 | 9.8 | 62.8 | 92.8 | 35.0 | 34.4 | 48.2 | 20.4 | 62.8 | 78.2 | 47.7
Falls(W00–W19) | 14.0 | 14.4 | 13.6 | 4.5 | 5.4 | 3.6 | 10.2 | 11.6 | 8.7 | 6.6 | 7.6 | 5.7 | 5.1 | 6.1 | 4.2 | 7.4 | 8.7 | * | 20.2 | 20.3 | 20.2
Accidental discharge of firearms(W32–W34) | 0.1 | 0.2 | 0.0 | 0.1 | 0.2 | * | * | * | * | * | * | * | 0.3 | 0.5 | * | * | * | * | 0.1 | 0.2 | 0.0
Accidental drowning and submersion(W65–W74) | 1.3 | 1.9 | 0.6 | 1.1 | 1.8 | 0.4 | 2.5 | 3.3 | 1.7 | 0.8 | 1.3 | 0.4 | 1.5 | 2.5 | 0.6 | * | * | * | 1.3 | 1.8 | 0.7
Accidental exposure to smoke, fire and flames(X00–X09) | 1.0 | 1.3 | 0.8 | 0.4 | 0.5 | 0.3 | 1.4 | 1.9 | * | 0.3 | 0.3 | 0.3 | 1.6 | 2.0 | 1.3 | * | * | * | 1.2 | 1.5 | 1.0
Accidental poisoning and exposure to noxious substances(X40–X49) | 30.9 | 44.8 | 17.2 | 22.2 | 35.4 | 8.6 | 68.8 | 91.3 | 46.7 | 4.9 | 8.4 | 1.7 | 47.5 | 73.1 | 23.7 | 18.4 | 28.9 | 7.6 | 32.5 | 45.3 | 19.9
Other and unspecified nontransport accidents and their sequelae(W20–W31,W35–W64,W75–W99,X10–X39,X50–X59,Y86) | 6.1 | 7.5 | 4.6 | 2.8 | 4.0 | 1.6 | 9.7 | 13.6 | 5.8 | 2.1 | 2.5 | 1.6 | 6.8 | 8.6 | 5.1 | 5.7 | * | * | 7.4 | 9.1 | 5.8
Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 14.8 | 23.8 | 6.1 | 8.0 | 12.8 | 3.2 | 26.8 | 39.7 | 14.3 | 7.2 | 10.5 | 4.1 | 9.1 | 15.2 | 3.5 | 14.9 | 23.3 | 6.4 | 19.1 | 30.6 | 7.7
Intentional self-harm (suicide) by discharge of firearms(X72–X74) | 8.1 | 14.2 | 2.1 | 3.3 | 5.7 | 0.7 | 10.6 | 18.5 | 2.8 | 1.8 | 3.3 | 0.4 | 5.3 | 9.6 | 1.4 | 3.8 | 6.2 | * | 11.1 | 19.4 | 2.9
Intentional self-harm (suicide) by other and unspecified means and their sequelae(*U03,X60–X71,X75–X84,Y87.0) | 6.7 | 9.5 | 4.0 | 4.8 | 7.1 | 2.4 | 16.3 | 21.1 | 11.5 | 5.4 | 7.2 | 3.7 | 3.8 | 5.6 | 2.1 | 11.2 | 17.1 | * | 8.0 | 11.2 | 4.8
Assault (homicide)(*U01–^*^U02,X85–Y09,Y87.1) | 7.5 | 12.1 | 2.9 | 7.0 | 11.4 | 2.5 | 15.9 | 25.2 | 6.9 | 1.5 | 2.1 | 1.0 | 31.5 | 56.1 | 8.6 | 8.2 | 13.7 | * | 3.0 | 4.2 | 1.9
Assault (homicide) by discharge of firearms(*U01.4,X93–X95) | 5.9 | 9.9 | 1.9 | 5.5 | 9.2 | 1.7 | 9.3 | 15.5 | 3.2 | 1.0 | 1.4 | 0.6 | 27.5 | 50.1 | 6.6 | 5.8 | 10.6 | * | 2.0 | 2.8 | 1.1
Assault (homicide) by other and unspecified means and their sequelae(*U01.0–^*^U01.3,^*^U01.5–^*^U01.9,^*^U02,X85–X92,X96–Y09,Y87.1) | 1.6 | 2.1 | 1.0 | 1.5 | 2.2 | 0.9 | 6.7 | 9.8 | 3.7 | 0.6 | 0.7 | 0.5 | 3.9 | 6.1 | 2.0 | * | * | * | 1.1 | 1.4 | 0.8
Legal intervention(Y35,Y89.0) | 0.2 | 0.5 | 0.0 | 0.3 | 0.6 | * | 1.4 | 2.8 | * | * | * | * | 0.5 | 0.9 | * | * | * | * | 0.2 | 0.4 | 0.0
Events of undetermined intent(Y10–Y34,Y87.2,Y89.9) | 1.7 | 2.2 | 1.2 | 0.9 | 1.3 | 0.5 | 4.3 | 5.8 | 2.7 | 0.5 | 0.7 | 0.3 | 3.2 | 4.6 | 1.9 | * | * | * | 1.7 | 2.2 | 1.3
Discharge of firearms, undetermined intent(Y22–Y24) | 0.1 | 0.2 | 0.1 | 0.1 | 0.1 | * | * | * | * | * | * | * | 0.3 | 0.5 | 0.1 | * | * | * | 0.1 | 0.2 | 0.1
Other and unspecified events of undetermined intent and their sequelae(Y10–Y21,Y25–Y34,Y87.2,Y89.9) | 1.6 | 2.0 | 1.1 | 0.8 | 1.1 | 0.4 | 3.9 | 5.3 | 2.5 | 0.5 | 0.7 | 0.3 | 2.9 | 4.1 | 1.8 | * | * | * | 1.6 | 2.0 | 1.2
Operations of war and their sequelae(Y36,Y89.1) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Complications of medical and surgical care(Y40–Y84,Y88) | 1.1 | 1.2 | 1.1 | 0.5 | 0.5 | 0.5 | 1.3 | * | * | 0.4 | 0.4 | 0.4 | 1.4 | 1.4 | 1.4 | * | * | * | 1.3 | 1.4 | 1.3
Enterocolitis due to Clostridium difficile(A04.7)^4^ | 1.3 | 1.1 | 1.4 | 0.5 | 0.5 | 0.6 | 1.2 | * | 1.9 | 0.5 | 0.5 | 0.6 | 1.0 | 1.0 | 1.0 | * | * | * | 1.7 | 1.4 | 1.9
COVID-19(U07.1)^4^ | 56.0 | 62.1 | 49.9 | 32.2 | 36.9 | 27.3 | 69.8 | 71.9 | 67.8 | 26.9 | 31.9 | 22.2 | 52.0 | 53.3 | 50.9 | 44.8 | 48.8 | 40.7 | 69.0 | 77.0 | 61.2
Dementia-related causes^4^ | 87.9 | 59.0 | 116.3 | 30.2 | 19.2 | 41.4 | 37.1 | 25.1 | 48.8 | 37.4 | 25.2 | 48.8 | 56.1 | 38.0 | 72.8 | 31.8 | 21.8 | 42.0 | 122.4 | 82.3 | 162.0
Drug-induced deaths^4^ | 33.6 | 47.6 | 19.9 | 22.9 | 35.8 | 9.6 | 67.8 | 86.9 | 49.1 | 5.8 | 9.3 | 2.6 | 51.0 | 77.9 | 26.1 | 21.5 | 32.3 | 10.5 | 36.0 | 48.8 | 23.4
Drug overdose deaths^4^ | 32.4 | 45.9 | 19.1 | 22.2 | 34.8 | 9.2 | 63.7 | 81.8 | 46.0 | 5.6 | 9.0 | 2.5 | 49.3 | 75.3 | 25.2 | 19.7 | 29.9 | 9.2 | 34.6 | 47.0 | 22.5
Alcohol-induced deaths^4^ | 15.4 | 22.0 | 8.8 | 11.7 | 18.7 | 4.6 | 78.6 | 98.5 | 59.2 | 3.3 | 5.5 | 1.2 | 10.3 | 15.0 | 6.0 | 6.9 | 10.6 | * | 18.4 | 25.8 | 11.1
Firearm-related injuries^4^ | 14.5 | 25.0 | 4.1 | 9.2 | 15.7 | 2.5 | 21.9 | 37.7 | 6.4 | 2.9 | 4.9 | 1.0 | 33.8 | 61.4 | 8.2 | 10.2 | 18.0 | * | 13.4 | 22.9 | 4.1

0.0 Quantity more than zero but less than 0.05.

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

… Category not applicable.

^1^Includes deaths with origin not stated, origin not classifiable, and two or more races reported; see Technical Notes.

^2^Includes people of Hispanic origin of any race; see Technical Notes.

^3^Only one race was reported on the death certificate; see Technical Notes.

^4^Included in selected categories above. For list of ICD–10 codes included, see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 11 Age-adjusted death rate for 113 selected causes, Enterocolitis due to Clostridium difficile, COVID-19, dementia-related causes, drug-induced causes, alcohol-induced causes, and firearm-related injuries, by Hispanic origin and race and sex: United States, 2022

[Age-adjusted rates are per 100,000 U.S. standard population; see Technical Notes in this report. Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards. Data for some Hispanic-origin and race categories should be interpreted with caution because of inconsistencies in reporting these items on death certificates and surveys; see Technical Notes. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10); see Technical Notes]

Cause of death (based on ICD–10) | Total^1^ | | | Hispanic^2^ | | | Non-Hispanic, single race^3^
Cause of death (based on ICD–10) | Total^1^ | | | Hispanic^2^ | | | American Indian and Alaska Native | | | Asian | | | Black | | | Native Hawaiian or Other Pacific Islander | | | White
Cause of death (based on ICD–10) | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All causes | 798.8 | 954.5 | 666.1 | 614.7 | 748.8 | 498.4 | 947.9 | 1,084.3 | 816.1 | 417.5 | 501.7 | 350.7 | 1,002.8 | 1,257.5 | 809.0 | 782.0 | 859.5 | 705.4 | 822.2 | 972.1 | 692.7
Salmonella infections(A01–A02) | 0.0 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | 0.0 | 0.0 | 0.0
Shigellosis and amebiasis(A03,A06) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Certain other intestinal infections(A04,A07–A09) | 1.8 | 1.7 | 1.8 | 1.4 | 1.5 | 1.4 | 2.3 | 1.7 | 2.6 | 0.9 | 0.8 | 0.9 | 1.9 | 2.1 | 1.8 | * | * | * | 1.8 | 1.7 | 1.9
Tuberculosis(A16–A19) | 0.1 | 0.2 | 0.1 | 0.2 | 0.4 | 0.1 | * | * | * | 0.7 | 1.1 | 0.4 | 0.2 | 0.3 | 0.1 | * | * | * | 0.1 | 0.1 | 0.1
Respiratory tuberculosis(A16) | 0.1 | 0.1 | 0.0 | 0.2 | 0.3 | * | * | * | * | 0.5 | 0.9 | 0.2 | 0.1 | 0.2 | 0.1 | * | * | * | 0.0 | 0.0 | 0.0
Other tuberculosis(A17–A19) | 0.0 | 0.0 | 0.0 | 0.1 | 0.1 | * | * | * | * | 0.1 | * | * | 0.1 | * | * | * | * | * | 0.0 | 0.0 | 0.0
Whooping cough(A37) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Scarlet fever and erysipelas(A38,A46) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Meningococcal infection(A39) | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Septicemia(A40–A41) | 10.1 | 11.4 | 9.1 | 7.4 | 8.3 | 6.6 | 12.5 | 13.0 | 12.1 | 4.5 | 5.6 | 3.7 | 17.3 | 20.2 | 15.5 | 11.2 | 11.1 | 11.2 | 9.9 | 11.1 | 9.0
Syphilis(A50–A53) | 0.0 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | * | 0.0 | * | * | * | * | * | * | * | *
Acute poliomyelitis(A80) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Arthropod-borne viralencephalitis(A83–A84, A85.2) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Measles(B05) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Viral hepatitis(B15–B19) | 0.7 | 0.9 | 0.5 | 0.9 | 1.2 | 0.7 | 1.9 | 1.8 | 2.0 | 0.9 | 1.1 | 0.6 | 0.9 | 1.2 | 0.6 | * | * | * | 0.7 | 0.8 | 0.5
Human immunodeficiencyvirus (HIV) disease(B20–B24) | 1.3 | 2.1 | 0.6 | 1.3 | 2.2 | 0.5 | 1.7 | 2.5 | * | 0.2 | 0.5 | * | 5.4 | 8.1 | 3.1 | * | * | * | 0.7 | 1.1 | 0.2
Malaria(B50–B54) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Other and unspecifiedinfectious and parasitic diseases and their sequelae(A00,A05,A20–A36,A42–A44,A48–A49,A54–A79,A81–A82,A85.0–A85.1,A85.8,A86–B04,B06–B09,B25–B49,B55–B99,U07.1) | 47.3 | 60.0 | 37.7 | 49.5 | 65.5 | 37.4 | 71.0 | 77.9 | 65.3 | 27.2 | 36.7 | 20.3 | 57.4 | 71.0 | 49.0 | 52.8 | 63.4 | 44.3 | 46.7 | 59.2 | 37.2
Malignant neoplasms(C00–C97) | 142.3 | 167.3 | 124.2 | 104.3 | 121.9 | 92.2 | 118.2 | 122.7 | 115.0 | 90.1 | 105.0 | 79.5 | 165.0 | 202.9 | 142.2 | 141.0 | 139.8 | 143.8 | 149.0 | 174.6 | 130.0
Malignant neoplasms of lip, oral cavity and pharynx(C00–C14) | 2.7 | 4.2 | 1.5 | 1.5 | 2.4 | 0.8 | 2.4 | 3.1 | 1.9 | 2.1 | 3.3 | 1.2 | 2.6 | 4.5 | 1.3 | 4.0 | * | * | 3.0 | 4.6 | 1.6
Malignant neoplasm of esophagus(C15) | 3.7 | 6.4 | 1.4 | 1.8 | 3.1 | 0.7 | 2.6 | 4.1 | 1.4 | 1.6 | 2.7 | 0.6 | 2.6 | 4.4 | 1.4 | * | * | * | 4.3 | 7.4 | 1.6
Malignant neoplasm of stomach(C16) | 2.6 | 3.4 | 2.0 | 4.4 | 5.4 | 3.6 | 3.3 | 3.8 | 2.9 | 3.9 | 5.2 | 2.9 | 4.4 | 6.1 | 3.3 | 4.1 | * | * | 1.9 | 2.6 | 1.4
Malignant neoplasms of colon, rectum and anus(C18–C21) | 13.0 | 15.3 | 11.0 | 10.7 | 13.1 | 8.8 | 13.1 | 15.2 | 11.2 | 9.1 | 11.2 | 7.4 | 16.5 | 20.6 | 13.6 | 12.6 | 14.3 | 11.4 | 13.2 | 15.4 | 11.3
Malignant neoplasms of liver and intrahepatic bile ducts(C22) | 6.6 | 9.3 | 4.2 | 8.8 | 12.1 | 6.0 | 8.3 | 9.7 | 7.1 | 7.5 | 10.8 | 4.8 | 7.7 | 12.0 | 4.6 | 10.6 | 15.2 | 6.2 | 6.0 | 8.4 | 3.9
Malignant neoplasm of pancreas(C25) | 11.1 | 12.9 | 9.7 | 8.8 | 9.5 | 8.0 | 9.1 | 8.5 | 9.5 | 7.4 | 8.0 | 6.9 | 13.5 | 15.5 | 12.1 | 10.6 | 8.8 | 12.1 | 11.5 | 13.4 | 9.9
Malignant neoplasm of larynx(C32) | 0.9 | 1.6 | 0.3 | 0.5 | 1.0 | 0.1 | 0.8 | * | * | 0.3 | 0.5 | * | 1.4 | 2.6 | 0.5 | * | * | * | 0.9 | 1.6 | 0.4
Malignant neoplasms of trachea, bronchus and lung(C33–C34) | 30.1 | 35.2 | 26.0 | 13.6 | 17.6 | 10.7 | 24.7 | 24.2 | 25.2 | 17.8 | 22.6 | 14.2 | 32.3 | 43.3 | 24.8 | 29.0 | 29.1 | 29.1 | 33.2 | 37.9 | 29.5
Malignant melanoma of skin(C43) | 2.0 | 2.8 | 1.3 | 0.6 | 0.7 | 0.5 | * | * | * | 0.3 | 0.4 | 0.2 | 0.3 | 0.4 | 0.3 | * | * | * | 2.6 | 3.7 | 1.7
Malignant neoplasm of breast(C50) | 10.3 | 0.2 | 18.8 | 7.4 | 0.1 | 13.5 | 7.7 | * | 14.4 | 6.4 | * | 11.5 | 15.2 | 0.5 | 26.1 | 10.6 | * | 20.4 | 10.3 | 0.2 | 19.0
Malignant neoplasm of cervix uteri(C53) | 1.1 | … | 2.1 | 1.2 | … | 2.2 | 1.3 | … | 2.6 | 0.7 | … | 1.3 | 1.5 | … | 2.8 | 3.1 | … | 6.3 | 1.0 | … | 2.0
Malignant neoplasms of corpus uteri and uterus, part unspecified(C54–C55) | 2.9 | … | 5.4 | 2.4 | … | 4.5 | 2.0 | … | 3.8 | 2.0 | … | 3.5 | 5.9 | … | 10.2 | 5.3 | … | 10.2 | 2.6 | … | 4.9
Malignant neoplasm of ovary(C56) | 3.1 | … | 5.8 | 2.6 | … | 4.7 | 2.2 | … | 4.1 | 2.4 | … | 4.3 | 3.0 | … | 5.2 | 3.3 | … | 6.5 | 3.3 | … | 6.1
Malignant neoplasm of prostate(C61) | 7.7 | 18.6 | … | 6.3 | 15.4 | … | 5.2 | 12.0 | … | 3.4 | 8.3 | … | 13.7 | 36.5 | … | 6.3 | 13.8 | … | 7.5 | 17.8 | …
Malignant neoplasms of kidney and renal pelvis(C64–C65) | 3.4 | 5.0 | 2.1 | 3.0 | 4.5 | 1.8 | 4.7 | 6.8 | 3.1 | 1.7 | 2.4 | 1.2 | 3.3 | 5.0 | 2.1 | * | * | * | 3.6 | 5.2 | 2.2
Malignant neoplasm of bladder(C67) | 4.1 | 6.9 | 2.0 | 2.1 | 3.6 | 1.0 | 2.2 | 3.0 | 1.5 | 1.7 | 2.8 | 0.9 | 3.3 | 5.4 | 2.0 | * | * | * | 4.6 | 7.8 | 2.2
Malignant neoplasms of meninges, brain and other parts of central nervous system(C70–C72) | 4.3 | 5.2 | 3.5 | 3.0 | 3.4 | 2.6 | 2.3 | 3.1 | 1.6 | 2.2 | 2.7 | 1.7 | 2.8 | 3.4 | 2.4 | 4.5 | * | * | 5.1 | 6.2 | 4.1
Malignant neoplasms of lymphoid, hematopoietic and related tissue(C81–C96) | 13.6 | 17.6 | 10.4 | 10.8 | 13.4 | 8.9 | 7.9 | 8.2 | 7.7 | 8.1 | 10.7 | 6.3 | 14.3 | 18.6 | 11.4 | 11.8 | 12.4 | 11.0 | 14.2 | 18.5 | 10.8
Hodgkin disease(C81) | 0.3 | 0.3 | 0.2 | 0.3 | 0.5 | 0.2 | * | * | * | 0.1 | * | * | 0.2 | 0.3 | 0.1 | * | * | * | 0.3 | 0.4 | 0.2
Non-Hodgkin lymphoma(C82–C85) | 4.7 | 6.1 | 3.6 | 4.1 | 5.0 | 3.4 | 2.5 | 2.7 | 2.4 | 3.4 | 4.6 | 2.5 | 3.5 | 4.7 | 2.6 | 3.7 | * | * | 5.0 | 6.5 | 3.8
Leukemia(C91–C95) | 5.6 | 7.4 | 4.3 | 4.0 | 5.0 | 3.3 | 2.8 | 2.8 | 2.8 | 3.1 | 4.2 | 2.3 | 4.9 | 6.5 | 3.9 | 5.6 | * | * | 6.1 | 8.0 | 4.6
Multiple myeloma and immunoproliferative neoplasms(C88,C90) | 2.9 | 3.7 | 2.3 | 2.4 | 2.9 | 2.0 | 2.4 | 2.6 | 2.3 | 1.4 | 1.6 | 1.3 | 5.6 | 7.0 | 4.7 | * | * | * | 2.8 | 3.6 | 2.1
Other and unspecified malignant neoplasms of lymphoid, hematopoietic and related tissue(C96) | 0.0 | 0.1 | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | 0.0 | 0.0 | 0.0
All other and unspecified malignant neoplasms(C17,C23–C24,C26–C31,C37–C41,C44–C49,C51–C52,C57–C60,C62–C63,C66,C68–C69,C73–C80,C97) | 19.2 | 22.6 | 16.6 | 14.9 | 16.4 | 13.7 | 17.6 | 18.9 | 16.3 | 11.6 | 13.2 | 10.3 | 20.7 | 24.2 | 18.3 | 16.5 | 18.1 | 15.0 | 20.1 | 23.8 | 17.3
In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 3.8 | 4.7 | 3.2 | 2.4 | 2.9 | 2.1 | 2.7 | 2.7 | 2.6 | 2.1 | 2.4 | 1.9 | 3.8 | 4.6 | 3.5 | * | * | * | 4.1 | 5.2 | 3.4
Anemias(D50–D64) | 1.5 | 1.6 | 1.4 | 1.0 | 1.1 | 0.9 | 1.4 | * | 1.4 | 0.8 | 0.9 | 0.7 | 3.0 | 3.3 | 2.9 | * | * | * | 1.3 | 1.4 | 1.2
Diabetes mellitus(E10–E14) | 24.1 | 30.5 | 18.8 | 28.3 | 34.7 | 22.9 | 47.7 | 55.1 | 40.8 | 17.2 | 21.5 | 13.9 | 42.9 | 52.8 | 35.5 | 49.9 | 53.8 | 46.0 | 21.3 | 27.6 | 16.0
Nutritional deficiencies(E40–E64) | 5.0 | 4.6 | 5.3 | 3.2 | 3.1 | 3.2 | 5.1 | 4.3 | 5.7 | 2.2 | 2.0 | 2.4 | 5.6 | 5.9 | 5.2 | * | * | * | 5.4 | 4.8 | 5.8
Malnutrition(E40–E46) | 4.9 | 4.4 | 5.2 | 3.1 | 3.1 | 3.2 | 4.8 | 3.9 | 5.5 | 2.2 | 2.0 | 2.3 | 5.4 | 5.8 | 5.1 | * | * | * | 5.3 | 4.7 | 5.6
Other nutritional deficiencies(E50–E64) | 0.1 | 0.1 | 0.1 | 0.1 | * | * | * | * | * | * | * | * | 0.1 | * | 0.1 | * | * | * | 0.1 | 0.1 | 0.1
Meningitis(G00,G03) | 0.2 | 0.2 | 0.1 | 0.1 | 0.2 | 0.1 | * | * | * | 0.1 | 0.2 | * | 0.3 | 0.4 | 0.2 | * | * | * | 0.1 | 0.2 | 0.1
Parkinson disease(G20–G21) | 9.5 | 14.2 | 6.3 | 6.9 | 9.9 | 5.0 | 4.8 | 6.1 | 3.8 | 6.0 | 8.7 | 4.1 | 5.2 | 8.0 | 3.5 | * | * | * | 10.7 | 15.8 | 7.0
Alzheimer disease(G30) | 28.9 | 23.0 | 32.6 | 27.0 | 21.4 | 30.3 | 15.1 | 11.7 | 17.6 | 16.4 | 13.1 | 18.4 | 26.9 | 23.0 | 28.8 | 20.9 | 12.3 | 26.9 | 30.4 | 24.0 | 34.5
Major cardiovascular diseases(I00–I78) | 223.0 | 272.4 | 182.0 | 163.4 | 201.3 | 132.1 | 191.9 | 225.6 | 161.2 | 126.7 | 154.3 | 104.5 | 301.0 | 377.0 | 244.5 | 245.3 | 274.1 | 215.9 | 226.8 | 276.4 | 185.1
Diseases of heart(I00–I09,I11,I13,I20–I51) | 167.2 | 213.5 | 129.5 | 114.6 | 147.8 | 87.7 | 147.9 | 183.9 | 116.2 | 84.2 | 109.1 | 64.6 | 216.9 | 281.3 | 169.5 | 173.2 | 201.8 | 143.7 | 173.1 | 220.5 | 133.9
Acute rheumatic fever and chronic rheumatic heart diseases(I00–I09) | 1.0 | 0.8 | 1.2 | 0.6 | 0.6 | 0.7 | 1.2 | * | * | 0.7 | 0.6 | 0.7 | 0.9 | 0.7 | 1.0 | * | * | * | 1.1 | 0.9 | 1.3
Hypertensive heart disease(I11) | 17.3 | 19.9 | 14.8 | 11.9 | 14.2 | 9.9 | 19.8 | 23.5 | 16.3 | 8.0 | 8.9 | 7.2 | 29.0 | 36.7 | 22.8 | 15.4 | 17.8 | 12.6 | 17.0 | 19.2 | 14.7
Hypertensive heart and renal disease(I13) | 3.9 | 4.4 | 3.5 | 2.6 | 3.0 | 2.2 | 5.6 | 6.0 | 5.4 | 1.8 | 2.0 | 1.6 | 6.5 | 8.0 | 5.4 | 4.3 | * | * | 3.8 | 4.2 | 3.4
Ischemic heart diseases(I20–I25) | 87.6 | 121.9 | 60.3 | 66.2 | 90.7 | 46.7 | 76.5 | 102.5 | 54.2 | 50.8 | 70.8 | 35.2 | 104.4 | 144.1 | 75.8 | 94.1 | 115.5 | 72.2 | 90.9 | 126.8 | 61.9
Acute myocardial infarction(I21–I22) | 24.5 | 33.3 | 17.2 | 18.4 | 24.3 | 13.5 | 22.3 | 29.4 | 16.2 | 14.5 | 19.8 | 10.2 | 28.5 | 38.2 | 21.5 | 27.1 | 29.3 | 24.2 | 25.8 | 35.3 | 17.7
Other acute ischemic heart diseases(I24) | 1.1 | 1.5 | 0.9 | 0.6 | 0.9 | 0.4 | 1.2 | 1.4 | * | 0.5 | 0.7 | 0.4 | 1.8 | 2.6 | 1.3 | * | * | * | 1.2 | 1.5 | 0.9
Other forms of chronic ischemic heart disease(I20,I25) | 62.0 | 87.1 | 42.3 | 47.2 | 65.6 | 32.8 | 53.0 | 71.7 | 37.0 | 35.8 | 50.3 | 24.6 | 74.0 | 103.4 | 53.0 | 66.4 | 85.3 | 47.7 | 64.0 | 90.1 | 43.2
Atherosclerotic cardiovascular disease, so described(I25.0) | 19.1 | 27.1 | 12.3 | 15.5 | 22.6 | 9.4 | 20.2 | 27.3 | 13.7 | 10.7 | 15.3 | 6.9 | 29.6 | 43.4 | 19.0 | 19.4 | 26.4 | 12.3 | 18.7 | 26.3 | 12.1
All other forms of chronic ischemic heart disease(I20,I25.1–I25.9) | 42.8 | 60.0 | 30.0 | 31.7 | 43.0 | 23.4 | 32.8 | 44.4 | 23.3 | 25.2 | 35.0 | 17.7 | 44.4 | 60.0 | 34.0 | 47.0 | 58.9 | 35.4 | 45.2 | 63.8 | 31.2
Other heart diseases(I26–I51) | 57.4 | 66.5 | 49.9 | 33.2 | 39.3 | 28.3 | 44.7 | 50.6 | 39.0 | 22.9 | 26.7 | 19.9 | 76.2 | 91.8 | 64.5 | 56.8 | 62.8 | 51.1 | 60.3 | 69.3 | 52.6
Acute and subacute endocarditis(I33) | 0.4 | 0.6 | 0.3 | 0.3 | 0.4 | 0.2 | * | * | * | 0.2 | 0.3 | * | 0.6 | 0.8 | 0.4 | * | * | * | 0.5 | 0.6 | 0.4
Diseases of pericardium and acute myocarditis(I30–I31,I40) | 0.3 | 0.4 | 0.3 | 0.3 | 0.2 | 0.2 | * | * | * | 0.1 | 0.3 | * | 0.5 | 0.5 | 0.5 | * | * | * | 0.3 | 0.3 | 0.3
Heart failure(I50) | 21.0 | 24.2 | 18.5 | 12.6 | 15.0 | 11.0 | 14.4 | 16.9 | 12.1 | 8.1 | 9.7 | 7.0 | 26.7 | 32.1 | 22.7 | 17.1 | 19.8 | 14.3 | 22.1 | 25.3 | 19.6
All other forms of heart disease(I26–I28,I34–I38,I42–I49,I51) | 35.7 | 41.3 | 30.8 | 20.0 | 23.7 | 16.8 | 29.1 | 32.7 | 25.5 | 14.5 | 16.5 | 12.8 | 48.4 | 58.4 | 40.8 | 38.9 | 42.0 | 36.2 | 37.4 | 43.1 | 32.4
Essential hypertension and hypertensive renal disease(I10,I12,I15) | 10.3 | 11.2 | 9.4 | 9.4 | 10.8 | 8.3 | 9.0 | 9.3 | 8.6 | 8.9 | 9.7 | 8.2 | 19.1 | 22.6 | 16.4 | 11.8 | 13.4 | 10.2 | 9.4 | 9.9 | 8.7
Cerebrovascular diseases(I60–I69) | 39.5 | 40.5 | 38.2 | 35.3 | 37.6 | 33.0 | 30.3 | 26.8 | 32.6 | 30.3 | 31.6 | 29.0 | 57.2 | 63.5 | 52.2 | 52.7 | 50.0 | 55.4 | 38.3 | 38.6 | 37.5
Atherosclerosis(I70) | 0.9 | 1.1 | 0.8 | 0.7 | 0.9 | 0.6 | * | * | * | 0.6 | 0.6 | 0.6 | 1.0 | 1.2 | 0.8 | * | * | * | 1.0 | 1.1 | 0.8
Other diseases of circulatory system (I71–I78) | 5.0 | 6.2 | 4.0 | 3.3 | 4.2 | 2.5 | 4.2 | 4.9 | 3.5 | 2.6 | 3.4 | 2.0 | 6.8 | 8.5 | 5.5 | 7.0 | 8.2 | * | 5.1 | 6.4 | 4.1
Aortic aneurysm and dissection(I71) | 2.4 | 3.3 | 1.7 | 1.3 | 1.9 | 0.8 | 1.4 | 1.8 | * | 1.6 | 2.2 | 1.1 | 2.8 | 3.7 | 2.1 | 4.1 | * | * | 2.6 | 3.4 | 1.8
Other diseases of arteries, arterioles and capillaries(I72–I78) | 2.6 | 2.9 | 2.3 | 2.0 | 2.3 | 1.7 | 2.7 | 3.0 | 2.5 | 1.0 | 1.2 | 0.9 | 4.0 | 4.7 | 3.4 | * | * | * | 2.6 | 2.9 | 2.3
Other disorders of circulatory system(I80–I99) | 1.3 | 1.5 | 1.2 | 1.0 | 1.2 | 0.8 | 1.4 | 1.8 | * | 0.4 | 0.4 | 0.3 | 2.5 | 2.7 | 2.4 | * | * | * | 1.3 | 1.4 | 1.1
Influenza and pneumonia(J09–J18) | 11.3 | 13.5 | 9.7 | 9.9 | 11.9 | 8.4 | 15.8 | 17.2 | 14.6 | 8.3 | 10.4 | 6.9 | 13.1 | 16.7 | 10.7 | 10.8 | 9.6 | 11.9 | 11.4 | 13.5 | 9.9
Influenza(J09–J11) | 1.5 | 1.5 | 1.4 | 1.3 | 1.3 | 1.2 | 2.9 | 3.0 | 2.9 | 0.7 | 0.7 | 0.7 | 1.3 | 1.5 | 1.2 | * | * | * | 1.5 | 1.6 | 1.5
Pneumonia(J12–J18) | 9.8 | 12.0 | 8.3 | 8.6 | 10.6 | 7.2 | 12.9 | 14.2 | 11.7 | 7.7 | 9.7 | 6.2 | 11.8 | 15.2 | 9.5 | 7.7 | 7.3 | 8.1 | 9.8 | 11.9 | 8.4
Other acute lower respiratory infections(J20–J22,U04) | 0.1 | 0.1 | 0.1 | 0.1 | * | * | * | * | * | * | * | * | 0.1 | 0.1 | * | * | * | * | 0.1 | 0.1 | 0.1
Acute bronchitis and bronchiolitis(J20–J21) | 0.0 | 0.1 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | 0.1 | * | * | * | * | * | 0.0 | 0.0 | 0.0
Other and unspecified acute lower respiratory infections(J22,U04) | 0.0 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | 0.0 | 0.0 | 0.0
Chronic lower respiratory diseases(J40–J47) | 34.3 | 37.0 | 32.3 | 14.3 | 17.3 | 12.3 | 29.2 | 29.3 | 29.1 | 8.5 | 12.2 | 5.8 | 26.7 | 33.3 | 22.7 | 19.8 | 22.4 | 17.7 | 39.6 | 41.6 | 38.3
Bronchitis, chronic and unspecified(J40–J42) | 0.1 | 0.1 | 0.1 | 0.0 | * | * | * | * | * | * | * | * | 0.1 | * | 0.1 | * | * | * | 0.1 | 0.1 | 0.1
Emphysema(J43) | 1.8 | 2.2 | 1.5 | 0.6 | 0.9 | 0.4 | 1.7 | 2.0 | 1.5 | 0.6 | 1.1 | 0.3 | 1.2 | 1.8 | 0.9 | * | * | * | 2.2 | 2.5 | 1.9
Asthma(J45–J46) | 1.0 | 0.8 | 1.1 | 0.7 | 0.6 | 0.8 | 1.4 | * | 1.8 | 0.5 | 0.6 | 0.5 | 2.4 | 2.4 | 2.4 | * | * | * | 0.8 | 0.6 | 0.9
Other chronic lower respiratory diseases(J44,J47) | 31.4 | 34.0 | 29.6 | 12.9 | 15.7 | 11.0 | 25.9 | 26.1 | 25.7 | 7.2 | 10.5 | 4.9 | 23.0 | 29.1 | 19.3 | 17.4 | 19.2 | 15.7 | 36.6 | 38.5 | 35.4
Pneumoconioses and chemical effects(J60–J66,J68,U07.0) | 0.1 | 0.3 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | 0.2 | 0.4 | 0.0
Pneumonitis due to solids and liquids(J69) | 4.8 | 6.7 | 3.4 | 3.3 | 4.4 | 2.6 | 3.8 | 4.6 | 3.2 | 3.3 | 4.6 | 2.5 | 5.9 | 8.6 | 4.2 | * | * | * | 4.9 | 7.0 | 3.5
Other diseases of respiratory system(J00–J06,J30–J39,J67,J70–J98) | 11.4 | 13.7 | 9.7 | 9.7 | 11.7 | 8.3 | 11.8 | 12.9 | 10.8 | 6.3 | 7.8 | 5.2 | 11.5 | 13.4 | 10.1 | 6.3 | * | * | 12.0 | 14.3 | 10.3
Peptic ulcer(K25–K28) | 1.0 | 1.2 | 0.8 | 0.8 | 1.1 | 0.6 | 1.3 | * | * | 0.8 | 0.9 | 0.6 | 1.0 | 1.4 | 0.7 | * | * | * | 1.0 | 1.2 | 0.9
Diseases of appendix(K35–K38) | 0.1 | 0.1 | 0.1 | 0.1 | 0.1 | * | * | * | * | * | * | * | 0.2 | 0.3 | 0.1 | * | * | * | 0.1 | 0.1 | 0.1
Hernia(K40–K46) | 0.6 | 0.7 | 0.6 | 0.6 | 0.6 | 0.5 | 0.9 | * | * | 0.2 | * | 0.2 | 0.5 | 0.6 | 0.4 | * | * | * | 0.7 | 0.7 | 0.7
Chronic liver disease and cirrhosis(K70,K73–K74) | 13.8 | 18.0 | 10.0 | 17.0 | 23.3 | 10.9 | 64.7 | 71.3 | 58.2 | 4.1 | 5.8 | 2.7 | 8.9 | 11.9 | 6.5 | 7.4 | 10.3 | * | 14.7 | 18.6 | 10.9
Alcoholic liver disease(K70) | 8.1 | 11.2 | 5.2 | 9.1 | 14.7 | 3.9 | 49.9 | 57.6 | 42.7 | 1.8 | 3.0 | 0.9 | 4.9 | 6.8 | 3.4 | 4.2 | 6.6 | * | 8.7 | 11.6 | 6.0
Other chronic liver disease and cirrhosis(K73–K74) | 5.7 | 6.8 | 4.8 | 7.8 | 8.6 | 7.0 | 14.7 | 13.7 | 15.6 | 2.3 | 2.8 | 1.8 | 4.0 | 5.1 | 3.1 | 3.2 | * | * | 5.9 | 7.0 | 4.9
Cholelithiasis and other disorders of gallbladder(K80–K82) | 1.0 | 1.3 | 0.9 | 1.2 | 1.4 | 1.0 | 1.7 | * | 1.7 | 0.8 | 0.9 | 0.7 | 1.1 | 1.2 | 1.1 | * | * | * | 1.0 | 1.3 | 0.9
Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 13.8 | 16.7 | 11.6 | 12.4 | 14.9 | 10.5 | 17.1 | 19.3 | 15.3 | 9.3 | 11.5 | 7.6 | 26.9 | 32.3 | 23.3 | 20.0 | 21.0 | 19.5 | 12.5 | 15.3 | 10.4
Acute and rapidly progressive nephritic and nephrotic syndrome(N00–N01,N04) | 0.2 | 0.2 | 0.2 | 0.1 | 0.2 | 0.1 | * | * | * | 0.1 | * | * | 0.3 | 0.4 | 0.3 | * | * | * | 0.2 | 0.2 | 0.1
Chronic glomerulonephritis, nephritis and nephropathy not specified as acute or chronic, and renal sclerosis unspecified(N02–N03,N05–N07,N26) | 0.1 | 0.1 | 0.1 | 0.0 | * | * | * | * | * | 0.1 | * | * | 0.1 | * | 0.1 | * | * | * | 0.1 | 0.1 | 0.1
Renal failure(N17–N19) | 13.5 | 16.4 | 11.4 | 12.2 | 14.7 | 10.3 | 16.7 | 18.8 | 15.0 | 9.0 | 11.1 | 7.5 | 26.5 | 31.8 | 22.9 | 19.5 | 20.5 | 18.9 | 12.2 | 15.0 | 10.2
Other disorders of kidney(N25,N27) | 0.0 | 0.0 | 0.0 | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | 0.0 | * | *
Infections of kidney(N10–N12,N13.6,N15.1) | 0.3 | 0.2 | 0.3 | 0.3 | 0.2 | 0.4 | * | * | * | 0.1 | * | * | 0.3 | 0.3 | 0.3 | * | * | * | 0.3 | 0.2 | 0.3
Hyperplasia of prostate(N40) | 0.2 | 0.5 | … | 0.2 | 0.5 | … | * | * | … | 0.1 | 0.3 | … | 0.2 | 0.5 | … | * | * | … | 0.2 | 0.5 | …
Inflammatory diseases of female pelvic organs(N70–N76) | 0.0 | … | 0.1 | 0.1 | … | 0.1 | * | … | * | * | … | * | 0.1 | … | 0.2 | * | … | * | 0.0 | … | 0.1
Pregnancy, childbirth and the puerperium(O00–O99) | 0.4 | … | 0.9 | 0.3 | … | 0.7 | 1.1 | … | 2.2 | 0.2 | … | 0.4 | 1.0 | … | 1.9 | * | … | * | 0.3 | … | 0.7
Pregnancy with abortive outcome(O00–O07) | 0.0 | … | 0.0 | * | … | * | * | … | * | * | … | * | * | … | * | * | … | * | * | … | *
Other complications of pregnancy, childbirth and the puerperium(O10–O99) | 0.4 | … | 0.8 | 0.3 | … | 0.7 | 1.0 | … | 2.0 | 0.2 | … | 0.4 | 0.9 | … | 1.8 | * | … | * | 0.3 | … | 0.7
Certain conditions originating in the perinatal period(P00–P96) | 3.8 | 4.2 | 3.4 | 3.3 | 3.7 | 3.0 | 4.5 | 5.1 | 3.8 | 2.5 | 2.7 | 2.2 | 7.5 | 8.5 | 6.6 | 7.0 | 7.2 | * | 3.1 | 3.3 | 2.8
Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 3.2 | 3.3 | 3.1 | 2.8 | 2.8 | 2.7 | 4.0 | 4.0 | 3.9 | 1.5 | 1.6 | 1.3 | 3.8 | 4.0 | 3.6 | 3.9 | * | * | 3.4 | 3.5 | 3.2
Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified(R00–R99) | 8.9 | 10.0 | 7.7 | 5.7 | 7.1 | 4.3 | 13.2 | 17.6 | 9.2 | 3.7 | 4.2 | 3.2 | 13.1 | 15.8 | 10.8 | 8.5 | 9.4 | 7.7 | 8.9 | 9.7 | 7.9
All other diseases(residual) | 99.7 | 102.0 | 96.0 | 68.4 | 70.5 | 65.1 | 117.4 | 118.4 | 113.8 | 43.2 | 43.7 | 42.1 | 115.9 | 125.9 | 107.7 | 77.6 | 78.6 | 76.2 | 105.8 | 107.5 | 102.6
Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 64.0 | 89.5 | 39.4 | 48.9 | 73.7 | 23.7 | 131.2 | 174.8 | 88.3 | 19.0 | 27.4 | 11.6 | 80.7 | 123.2 | 43.7 | 49.4 | 71.0 | 27.6 | 67.9 | 91.7 | 44.5
Transport accidents(V01–V99,Y85) | 14.2 | 20.9 | 7.6 | 14.2 | 21.1 | 7.1 | 36.5 | 49.3 | 23.8 | 4.9 | 6.9 | 3.1 | 19.1 | 29.3 | 10.0 | 14.7 | 21.5 | 7.5 | 13.8 | 20.1 | 7.6
Motor vehicle accidents(V02–V04,V09.0,V09.2,V12–V14,V19.0–V19.2,V19.4–V19.6,V20–V79,V80.3–V80.5,V81.0–V81.1,V82.0–V82.1,V83–V86,V87.0–V87.8,V88.0–V88.8, V89.0,V89.2) | 13.3 | 19.5 | 7.3 | 13.4 | 19.9 | 6.8 | 34.5 | 46.6 | 22.5 | 4.6 | 6.3 | 3.0 | 18.2 | 27.7 | 9.6 | 13.6 | 20.2 | 6.5 | 12.9 | 18.6 | 7.2
Other land transport accidents(V01,V05–V06,V09.1,V09.3–V09.9,V10–V11,V15–V18,V19.3,V19.8–V19.9,V80.0–V80.2,V80.6–V80.9,V81.2–V81.9,V82.2–V82.9,V87.9, V88.9,V89.1,V89.3,V89.9) | 0.3 | 0.6 | 0.1 | 0.4 | 0.7 | 0.1 | 0.9 | * | * | 0.2 | 0.3 | * | 0.4 | 0.7 | 0.1 | * | * | * | 0.3 | 0.5 | 0.1
Water, air and space, and other and unspecified transport accidents and their sequelae(V90–V99,Y85) | 0.6 | 0.9 | 0.2 | 0.4 | 0.5 | 0.2 | 1.0 | * | * | 0.2 | 0.3 | * | 0.5 | 0.9 | 0.2 | * | * | * | 0.6 | 1.0 | 0.3
Nontransport accidents(W00–X59,Y86) | 49.8 | 68.6 | 31.7 | 34.7 | 52.6 | 16.6 | 94.7 | 125.5 | 64.6 | 14.1 | 20.5 | 8.6 | 61.6 | 93.9 | 33.8 | 34.7 | 49.5 | 20.1 | 54.1 | 71.6 | 36.9
Falls(W00–W19) | 11.2 | 13.8 | 9.2 | 6.9 | 9.2 | 5.0 | 10.2 | 12.6 | 8.0 | 6.4 | 8.4 | 4.9 | 5.6 | 8.0 | 3.9 | 8.5 | 11.4 | * | 12.7 | 15.2 | 10.7
Accidental discharge of firearms(W32–W34) | 0.2 | 0.3 | 0.0 | 0.1 | 0.1 | * | * | * | * | * | * | * | 0.3 | 0.5 | * | * | * | * | 0.1 | 0.2 | 0.0
Accidental drowning and submersion(W65–W74) | 1.2 | 1.8 | 0.6 | 1.1 | 1.8 | 0.4 | 2.5 | 3.3 | 1.8 | 0.8 | 1.3 | 0.4 | 1.5 | 2.5 | 0.7 | * | * | * | 1.2 | 1.7 | 0.7
Accidental exposure to smoke, fire and flames(X00–X09) | 0.9 | 1.1 | 0.7 | 0.5 | 0.6 | 0.3 | 1.5 | 2.0 | * | 0.3 | 0.3 | 0.2 | 1.6 | 2.1 | 1.2 | * | * | * | 0.9 | 1.2 | 0.8
Accidental poisoning and exposure to noxious substances(X40–X49) | 31.1 | 44.5 | 17.6 | 22.7 | 35.9 | 8.9 | 70.3 | 92.9 | 47.8 | 4.6 | 7.8 | 1.6 | 45.8 | 71.2 | 23.0 | 17.6 | 27.5 | 7.4 | 33.6 | 45.9 | 20.9
Other and unspecified nontransport accidents and their sequelae(W20–W31,W35–W64,W75–W99,X10–X39,X50–X59,Y86) | 5.2 | 7.1 | 3.6 | 3.4 | 5.0 | 2.0 | 9.7 | 13.7 | 5.8 | 2.0 | 2.7 | 1.4 | 6.9 | 9.6 | 4.9 | 5.7 | * | * | 5.5 | 7.4 | 3.7
Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 14.2 | 23.0 | 5.9 | 8.1 | 13.0 | 3.1 | 27.1 | 39.6 | 14.6 | 6.9 | 10.1 | 3.9 | 8.9 | 14.9 | 3.5 | 14.3 | 22.1 | 6.1 | 17.6 | 28.1 | 7.3
Intentional self-harm (suicide) by discharge of firearms(X72–X74) | 7.6 | 13.5 | 2.0 | 3.3 | 5.9 | 0.7 | 10.5 | 18.4 | 2.7 | 1.7 | 3.2 | 0.4 | 5.2 | 9.4 | 1.4 | 3.7 | 6.1 | * | 9.7 | 17.1 | 2.7
Intentional self-harm (suicide) by other and unspecified means and their sequelae(*U03,X60–X71,X75–X84,Y87.0) | 6.7 | 9.4 | 3.9 | 4.8 | 7.2 | 2.4 | 16.6 | 21.2 | 11.9 | 5.1 | 6.9 | 3.5 | 3.7 | 5.5 | 2.1 | 10.6 | 16.0 | * | 7.8 | 11.0 | 4.6
Assault (homicide)(*U01–^*^U02,X85–Y09,Y87.1) | 7.7 | 12.4 | 3.0 | 6.8 | 10.9 | 2.5 | 16.5 | 25.7 | 7.2 | 1.5 | 2.0 | 1.0 | 31.0 | 53.9 | 8.7 | 7.9 | 12.9 | * | 3.1 | 4.3 | 1.9
Assault (homicide) by discharge of firearms(*U01.4,X93–X95) | 6.2 | 10.2 | 2.0 | 5.2 | 8.6 | 1.6 | 9.6 | 15.6 | 3.5 | 0.9 | 1.3 | 0.5 | 27.0 | 47.9 | 6.7 | 5.5 | 9.9 | * | 2.1 | 3.0 | 1.2
Assault (homicide) by other and unspecified means and their sequelae(*U01.0–^*^U01.3,^*^U01.5–^*^U01.9,^*^U02,X85–X92,X96–Y09,Y87.1) | 1.6 | 2.1 | 1.0 | 1.6 | 2.3 | 0.9 | 6.9 | 10.1 | 3.7 | 0.5 | 0.6 | 0.5 | 4.0 | 6.0 | 2.0 | * | * | * | 1.1 | 1.4 | 0.8
Legal intervention(Y35,Y89.0) | 0.3 | 0.5 | 0.0 | 0.3 | 0.6 | * | 1.3 | 2.7 | * | * | * | * | 0.5 | 0.9 | * | * | * | * | 0.2 | 0.4 | 0.0
Events of undetermined intent(Y10–Y34,Y87.2,Y89.9) | 1.7 | 2.2 | 1.2 | 0.9 | 1.3 | 0.5 | 4.3 | 5.9 | 2.7 | 0.5 | 0.7 | 0.3 | 3.1 | 4.5 | 1.9 | * | * | * | 1.7 | 2.2 | 1.3
Discharge of firearms, undetermined intent(Y22–Y24) | 0.1 | 0.2 | 0.1 | 0.1 | 0.2 | * | * | * | * | * | * | * | 0.3 | 0.5 | 0.1 | * | * | * | 0.1 | 0.2 | 0.1
Other and unspecified events of undetermined intent and their sequelae(Y10–Y21,Y25–Y34,Y87.2,Y89.9) | 1.5 | 2.0 | 1.1 | 0.8 | 1.2 | 0.5 | 3.9 | 5.4 | 2.5 | 0.5 | 0.7 | 0.3 | 2.8 | 4.0 | 1.8 | * | * | * | 1.6 | 2.0 | 1.2
Operations of war and their sequelae(Y36,Y89.1) | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | * | *
Complications of medical and surgical care(Y40–Y84,Y88) | 0.9 | 1.0 | 0.8 | 0.7 | 0.8 | 0.6 | 1.2 | * | * | 0.4 | 0.5 | 0.3 | 1.4 | 1.5 | 1.4 | * | * | * | 0.9 | 1.0 | 0.8
Enterocolitis due to Clostridium difficile(A04.7)^4^ | 1.0 | 1.0 | 1.0 | 0.8 | 0.9 | 0.8 | 1.2 | * | 1.7 | 0.5 | 0.5 | 0.5 | 1.1 | 1.3 | 0.9 | * | * | * | 1.0 | 1.0 | 1.1
COVID-19(U07.1)^4^ | 44.5 | 56.7 | 35.4 | 47.2 | 62.8 | 35.6 | 65.9 | 73.1 | 60.1 | 25.3 | 34.5 | 18.6 | 53.9 | 66.5 | 46.2 | 48.9 | 58.7 | 41.2 | 43.9 | 55.9 | 34.8
Dementia-related causes^4^ | 70.4 | 59.7 | 76.8 | 54.3 | 45.7 | 59.2 | 39.8 | 31.5 | 45.5 | 36.1 | 30.0 | 39.8 | 67.8 | 62.5 | 69.9 | 42.5 | 31.9 | 50.2 | 75.2 | 63.4 | 82.6
Drug-induced deaths^4^ | 33.8 | 47.2 | 20.2 | 23.4 | 36.3 | 9.9 | 69.5 | 88.8 | 50.3 | 5.5 | 8.7 | 2.5 | 49.2 | 75.7 | 25.3 | 20.7 | 30.9 | 10.2 | 36.9 | 49.2 | 24.2
Drug overdose deaths^4^ | 32.6 | 45.6 | 19.4 | 22.7 | 35.2 | 9.5 | 65.2 | 83.4 | 47.1 | 5.3 | 8.4 | 2.4 | 47.5 | 73.3 | 24.5 | 18.8 | 28.3 | 8.9 | 35.6 | 47.6 | 23.3
Alcohol-induced deaths^4^ | 13.5 | 19.5 | 7.8 | 13.2 | 21.5 | 5.1 | 78.4 | 98.4 | 59.4 | 2.9 | 5.1 | 1.1 | 9.7 | 14.5 | 5.7 | 7.1 | 11.2 | * | 14.8 | 20.5 | 9.1
Firearm-related injuries^4^ | 14.2 | 24.6 | 4.1 | 8.9 | 15.2 | 2.4 | 22.2 | 37.7 | 6.7 | 2.7 | 4.6 | 1.0 | 33.2 | 59.0 | 8.3 | 9.8 | 17.1 | * | 12.2 | 20.7 | 3.9

0.0 Quantity more than zero but less than 0.05.

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

… Category not applicable.

^1^Includes deaths with origin not stated, origin not classifiable, and two or more races reported; see Technical Notes.

^2^Includes people of Hispanic origin of any race; see Technical Notes.

^3^Only one race was reported on the death certificate; see Technical Notes.

^4^Included in selected categories above. For list of ICD–10 codes included, see Technical Notes..

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 12 Number of deaths, death rate, and age-adjusted death rate for injury deaths, by mechanism and intent of death: United States, 2022

[Totals for selected causes of death differ from those shown in other tables that use standard mortality tabulation lists; see Technical Notes in this report. Rates are per 100,000 population; age-adjusted rates are per 100,000 U.S. standard population; see Technical Notes. Populations used for computing death rates are postcensal estimates based on the 2020 census estimated as of July 1, 2022; see Technical Notes. Numbers in brackets [ ] apply to the code or range of codes preceding them. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10); see Technical Notes]

Mechanism and intent of death (based on ICD–10) | Number | Rate | Age-adjusted rate^1^
All injury(*U01–^*^U03,V01–Y36,Y85–Y87,Y89) | 307,785 | 92.3 | 87.9
Unintentional(V01–X59,Y85–Y86) | 227,039 | 68.1 | 64.0
Suicide(*U03,X60–X84,Y87.0) | 49,476 | 14.8 | 14.2
Homicide(*U01–^*^U02,X85–Y09,Y87.1) | 24,849 | 7.5 | 7.7
Undetermined(Y10–Y34,Y87.2,Y89.9) | 5,604 | 1.7 | 1.7
Legal intervention/war(Y35–Y36,Y89[.0,.1]) | 817 | 0.2 | 0.3
Cut/pierce(W25–W29,W45–W46,X78,X99,Y28,Y35.4) | 3,011 | 0.9 | 0.9
Unintentional(W25–W29,W45–W46) | 201 | 0.1 | 0.0
Suicide(X78) | 970 | 0.3 | 0.3
Homicide(X99) | 1,800 | 0.5 | 0.5
Undetermined(Y28) | 40 | 0.0 | 0.0
Legal intervention/war(Y35.4) | – | * | *
Drowning(W65–W74,X71,X92,Y21) | 5,043 | 1.5 | 1.5
Unintentional(W65–W74) | 4,168 | 1.3 | 1.2
Suicide(X71) | 502 | 0.2 | 0.1
Homicide(X92) | 39 | 0.0 | 0.0
Undetermined(Y21) | 334 | 0.1 | 0.1
Fall(W00–W19,X80,Y01,Y30) | 47,984 | 14.4 | 11.6
Unintentional(W00–W19) | 46,630 | 14.0 | 11.2
Suicide(X80) | 1,245 | 0.4 | 0.4
Homicide(Y01) | 10 | * | *
Undetermined(Y30) | 99 | 0.0 | 0.0
Fire/hot object or substance(*U01.3,X00–X19,X76–X77,X97–X98,Y26–Y27,Y36.3)^2^ | 4,096 | 1.2 | 1.1
Unintentional(X00–X19) | 3,571 | 1.1 | 0.9
Suicide(X76–X77) | 193 | 0.1 | 0.1
Homicide(*U01.3,X97–X98) | 96 | 0.0 | 0.0
Undetermined(Y26–Y27) | 236 | 0.1 | 0.1
Legal intervention/war(Y36.3) | – | * | *
Fire/flame(X00–X09,X76,X97,Y26) | 3,999 | 1.2 | 1.0
Unintentional(X00–X09) | 3,478 | 1.0 | 0.9
Suicide(X76) | 193 | 0.1 | 0.1
Homicide(X97) | 93 | 0.0 | 0.0
Undetermined(Y26) | 235 | 0.1 | 0.1
Hot object/substance(X10–X19,X77,X98,Y27) | 97 | 0.0 | 0.0
Unintentional(X10–X19) | 93 | 0.0 | 0.0
Suicide(X77) | – | * | *
Homicide(X98) | 3 | * | *
Undetermined(Y27) | 1 | * | *
Firearm(*U01.4,W32–W34,X72–X74,X93–X95,Y22–Y24,Y35.0) | 48,204 | 14.5 | 14.2
Unintentional(W32–W34) | 463 | 0.1 | 0.2
Suicide(X72–X74) | 27,032 | 8.1 | 7.6
Homicide(*U01.4,X93–X95) | 19,651 | 5.9 | 6.2
Undetermined(Y22–Y24) | 415 | 0.1 | 0.1
Legal intervention/war(Y35.0) | 643 | 0.2 | 0.2
Machinery(W24,W30–W31)^3^ | 645 | 0.2 | 0.2
All transport(*U01.1,V01–V99,X82,Y03,Y32,Y36.1) | 48,332 | 14.5 | 14.0
Unintentional(V01–V99) | 48,043 | 14.4 | 13.9
Suicide(X82) | 169 | 0.1 | 0.0
Homicide(*U01.1,Y03) | 101 | 0.0 | 0.0
Undetermined(Y32) | 19 | * | *
Legal intervention/war(Y36.1) | – | * | *
Motor vehicle traffic(V02–V04[.1,.9],V09.2,V12–V14[.3–.9],V19[.4–.6],V20–V28[.3–.9],V29–V79[.4–.9],V80[.3–.5],V81.1,V82.1,V83–V86[.0–.3],V87[.0–.8],V89.2)^3^ | 44,534 | 13.4 | 12.9
Occupant(V30–V79[.4–.9],V83–V86[.0–.3])^3^ | 9,457 | 2.8 | 2.7
Motorcyclist(V20–V28[.3–.9],V29[.4–.9])^3^ | 5,905 | 1.8 | 1.7
Pedal cyclist(V12–V14[.3–.9],V19[.4–.6])^3^ | 928 | 0.3 | 0.2
Pedestrian(V02–V04[.1,.9],V09.2)^3^ | 8,233 | 2.5 | 2.4
Other(V80[.3–.5],V81.1,V82.1)^3^ | 9 | * | *
Unspecified(V87[.0–.8],V89.2)^3^ | 20,002 | 6.0 | 5.8
Pedal cyclist, other(V10–V11,V12–V14[.0–.2],V15–V18,V19[.0–.3,.8,.9])^3^ | 432 | 0.1 | 0.1
Pedestrian, other(V01,V02–V04[.0],V05,V06,V09[.0,.1,.3,.9])^3^ | 955 | 0.3 | 0.3
Other land transport(V20–V28[.0–.2],V29–V79[.0–.3],V80[.0–.2,.6–.9],V81–V82[.0,.2–.9],V83–V86[.4–.9],V87.9,V88[.0–.9], V89[.0,.1,.3,.9],X82,Y03,Y32) | 1,590 | 0.5 | 0.5
Unintentional(V20–V28[.0–.2],V29–V79[.0–.3],V80[.0–.2,.6–.9],V81–V82[.0,.2–.9],V83–V86[.4–.9],V87.9,V88[.0–.9],V89[.0,.1,.3,.9]) | 1,301 | 0.4 | 0.4
Suicide(X82) | 169 | 0.1 | 0.0
Homicide(Y03) | 101 | 0.0 | 0.0
Undetermined(Y32) | 19 | * | *
Other transport(*U01.1,V90–V99,Y36.1) | 821 | 0.2 | 0.2
Unintentional(V90–V99) | 821 | 0.2 | 0.2
Homicide(*U01.1) | – | * | *
Legal intervention/war(Y36.1) | – | * | *
Natural/environmental(W42–W43,W53–W64,W92–W99,X20–X39,X51–X57)^3^ | 3,140 | 0.9 | 0.8
Overexertion(X50)^3^ | 28 | 0.0 | 0.0
Poisoning(*U01[.6–.7],X40–X49,X60–X69,X85–X90,Y10–Y19,Y35.2) | 112,728 | 33.8 | 33.9
Unintentional(X40–X49) | 102,958 | 30.9 | 31.1
Suicide(X60–X69) | 6,150 | 1.8 | 1.7
Homicide(*U01[.6–.7],X85–X90) | 214 | 0.1 | 0.1
Undetermined(Y10–Y19) | 3,406 | 1.0 | 1.0
Legal intervention/war(Y35.2) | – | * | *
Struck by or against(W20–W22,W50–W52,X79,Y00,Y04,Y29,Y35.3) | 1,184 | 0.4 | 0.3
Unintentional(W20–W22,W50–W52) | 936 | 0.3 | 0.3
Suicide(X79) | 3 | * | *
Homicide(Y00,Y04) | 243 | 0.1 | 0.1
Undetermined(Y29) | 2 | * | *
Legal intervention/war(Y35.3) | – | * | *
Suffocation(W75–W84,X70,X91,Y20) | 20,197 | 6.1 | 5.9
Unintentional(W75–W84) | 7,416 | 2.2 | 2.0
Suicide(X70) | 12,247 | 3.7 | 3.7
Homicide(X91) | 375 | 0.1 | 0.1
Undetermined(Y20) | 159 | 0.0 | 0.0
Other specified, classifiable(*U01[.0,.2,.5],^*^U03.0,W23,W35–W41,W44, W49,W85–W91,X75,X81,X96,Y02,Y05–Y07,Y25,Y31,Y35[.1,.5],Y36[.0,.2,.4–.8],Y85) | 2,810 | 0.8 | 0.8
Unintentional(W23,W35–W41,W44,W49,W85–W91,Y85) | 1,859 | 0.6 | 0.5
Suicide(*U03.0,X75,X81) | 708 | 0.2 | 0.2
Homicide(*U01[.0,.2,.5],X96,Y02,Y05–Y07) | 187 | 0.1 | 0.0
Undetermined(Y25,Y31) | 37 | 0.0 | 0.0
Legal intervention/war(Y35[.1,.5],Y36[.0,.2,.4–.8]) | 19 | * | *
Other specified, not elsewhere classified(*U01.8,^*^U02,X58,X83,Y08,Y33,Y35.6,Y86–Y87,Y89[.0–.1]) | 2,906 | 0.9 | 0.8
Unintentional(X58,Y86) | 1,708 | 0.5 | 0.4
Suicide(X83,Y87.0) | 155 | 0.0 | 0.1
Homicide(*U01.8,^*^U02,Y08,Y87.1) | 630 | 0.2 | 0.2
Undetermined(Y33,Y87.2) | 260 | 0.1 | 0.1
Legal intervention/war(Y35.6,Y89[.0,.1]) | 153 | 0.0 | 0.1
Unspecified(*U01.9,^*^U03.9,X59,X84,Y09,Y34,Y35.7,Y36.9,Y89.9) | 7,477 | 2.2 | 1.9
Unintentional(X59) | 5,273 | 1.6 | 1.3
Suicide(*U03.9,X84) | 102 | 0.0 | 0.0
Homicide(*U01.9,Y09) | 1,503 | 0.5 | 0.5
Undetermined(Y34,Y89.9) | 597 | 0.2 | 0.2
Legal intervention/war (Y35.7,Y36.9) | 2 | * | *

0.0 Quantity more than zero but less than 0.05.

– Quantity zero.

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

^1^For method of computation, see Technical Notes.

^2^Codes U01.3 and Y36.3 cannot be divided separately into the subcategories shown below; therefore, subcategories may not add to the total.

^3^Intent of death is unintentional.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 13 Number of deaths, death rate, and age-adjusted death rate for age 15 and older, by marital status and sex: United States, 2022

[Rates are per 100,000 population in specified group; age-adjusted rates are per 100,000 U.S. standard population; see Technical Notes in this report. Population estimates used for computing death rates are based on the 2022 1-year American Community Survey adjusted to postcensal July 1, 2022, resident population control totals for the United States; see Technical Notes]

Marital status and sex | Age group | | | | | | | | Age-adjusted rate^2^
Marital status and sex | 15 and older^1^ | 15–24 | 25–34 | 35–44 | 45–54 | 55–64 | 65–74 | 75 and older | Age-adjusted rate^2^
| Number
Both sexes | 3,248,806 | 35,232 | 74,369 | 111,605 | 183,284 | 417,541 | 668,581 | 1,758,194 | …
Never married | 474,143 | 34,102 | 58,093 | 57,886 | 58,785 | 96,537 | 86,274 | 82,466 | …
Ever married | 2,745,678 | 1,066 | 15,801 | 52,299 | 121,648 | 313,397 | 573,038 | 1,668,429 | …
Married | 1,170,668 | 914 | 11,278 | 32,158 | 69,139 | 164,948 | 301,398 | 590,833 | …
Widowed | 998,284 | 23 | 323 | 1,526 | 5,935 | 31,929 | 104,198 | 854,350 | …
Divorced | 576,726 | 129 | 4,200 | 18,615 | 46,574 | 116,520 | 167,442 | 223,246 | …
Not stated | 28,985 | 64 | 475 | 1,420 | 2,851 | 7,607 | 9,269 | 7,299 | …
Male | 1,701,852 | 25,637 | 52,511 | 73,486 | 114,847 | 254,278 | 384,985 | 796,108 | …
Never married | 305,100 | 24,937 | 42,236 | 40,876 | 40,100 | 65,358 | 53,632 | 37,961 | …
Ever married | 1,376,213 | 653 | 9,957 | 31,638 | 72,725 | 183,202 | 324,503 | 753,535 | …
Married | 781,922 | 567 | 7,197 | 19,484 | 41,611 | 99,787 | 192,561 | 420,715 | …
Widowed | 290,488 | 10 | 141 | 628 | 2,362 | 12,026 | 36,209 | 239,112 | …
Divorced | 303,803 | 76 | 2,619 | 11,526 | 28,752 | 71,389 | 95,733 | 93,708 | …
Not stated | 20,539 | 47 | 318 | 972 | 2,022 | 5,718 | 6,850 | 4,612 | …
Female | 1,546,954 | 9,595 | 21,858 | 38,119 | 68,437 | 163,263 | 283,596 | 962,086 | …
Never married | 169,043 | 9,165 | 15,857 | 17,010 | 18,685 | 31,179 | 32,642 | 44,505 | …
Ever married | 1,369,465 | 413 | 5,844 | 20,661 | 48,923 | 130,195 | 248,535 | 914,894 | …
Married | 388,746 | 347 | 4,081 | 12,674 | 27,528 | 65,161 | 108,837 | 170,118 | …
Widowed | 707,796 | 13 | 182 | 898 | 3,573 | 19,903 | 67,989 | 615,238 | …
Divorced | 272,923 | 53 | 1,581 | 7,089 | 17,822 | 45,131 | 71,709 | 129,538 | …
Not stated | 8,446 | 17 | 157 | 448 | 829 | 1,889 | 2,419 | 2,687 | …
| Rate^3^
Both sexes | 1,186.0 | 79.7 | 164.4 | 253.4 | 452.8 | 991.1 | 1,972.3 | 7,349.0 | 1,213.6
Never married | 504.0 | 81.7 | 227.9 | 496.6 | 925.3 | 1,924.9 | 3,216.9 | 7,176.4 | 1,623.5
Ever married | 1,526.6 | 42.7 | 80.0 | 161.5 | 356.5 | 844.5 | 1,835.7 | 7,325.7 | 1,116.8
Married | 860.3 | 38.5 | 62.6 | 115.6 | 254.2 | 599.7 | 1,405.2 | 5,044.2 | 790.4
Widowed | 6,610.6 | * | 384.9 | 578.8 | 875.9 | 1,607.2 | 2,592.1 | 10,606.6 | 1,880.3
Divorced | 2,010.9 | 116.7 | 255.2 | 432.4 | 746.0 | 1,529.2 | 2,912.9 | 7,423.9 | 1,514.4
Male | 1,262.2 | 113.2 | 228.0 | 330.1 | 565.7 | 1,231.0 | 2,413.9 | 7,980.4 | 1,406.1
Never married | 608.2 | 115.4 | 300.4 | 627.3 | 1,157.1 | 2,392.0 | 4,026.3 | 8,438.6 | 1,983.4
Ever married | 1,625.5 | 62.2 | 111.0 | 200.9 | 432.0 | 1,022.1 | 2,220.1 | 7,910.3 | 1,266.7
Married | 1,132.8 | 56.8 | 87.2 | 141.3 | 300.0 | 711.1 | 1,704.5 | 6,197.4 | 964.7
Widowed | 8,310.0 | * | 590.5 | 790.5 | 1,247.4 | 2,298.6 | 3,784.8 | 13,929.2 | 2,579.3
Divorced | 2,502.2 | 169.9 | 377.4 | 615.1 | 1,035.3 | 2,119.5 | 4,051.7 | 9,179.9 | 2,006.1
Female | 1,112.0 | 44.5 | 98.4 | 175.0 | 339.2 | 760.4 | 1,580.0 | 6,897.5 | 1,043.0
Never married | 384.9 | 45.5 | 138.8 | 330.9 | 647.1 | 1,365.7 | 2,418.2 | 6,364.4 | 1,272.4
Ever married | 1,438.6 | 28.5 | 54.2 | 124.1 | 283.0 | 678.5 | 1,497.3 | 6,905.3 | 990.5
Married | 579.8 | 25.3 | 41.8 | 90.3 | 206.5 | 483.6 | 1,072.2 | 3,454.5 | 571.7
Widowed | 6,098.7 | * | 303.1 | 487.5 | 731.8 | 1,360.0 | 2,219.6 | 9,706.7 | 1,654.8
Divorced | 1,650.2 | 80.5 | 166.1 | 291.6 | 514.1 | 1,061.5 | 2,118.1 | 6,521.4 | 1,183.5

… Category not applicable.

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

^1^Excludes data for age not stated.

^2^Calculated based on age 25 and older. For method of computation, see Technical Notes.

^3^Data for marital status not stated are included in totals for both sexes, male, and female but are not distributed among specified marital status groups.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 14 Number of deaths, death rate, and age-adjusted death rate for ages 25–64, by educational attainment and sex: United States, 2022

[Rates are per 100,000 population in specified group; age-adjusted rates are per 100,000 U.S. standard population; see Technical Notes in this report. Population estimates used for computing death rates are based on the 2022 1-year American Community Survey adjusted to postcensal July 1, 2022, resident population control totals for the United States; see Technical Notes]

Education level and sex | Age group | | | | | Age-adjusted rate^2^
Education level and sex | 25–64^1^ | 25–34 | 35–44 | 45–54 | 55–64 | Age-adjusted rate^2^
| Number
Both sexes | 786,799 | 74,369 | 111,605 | 183,284 | 417,541 | …
Less than high school diploma or GED | 137,271 | 13,575 | 20,478 | 31,644 | 71,574 | …
High school diploma or GED | 358,700 | 36,679 | 50,390 | 80,137 | 191,494 | …
Some college or collegiate degree | 271,100 | 23,155 | 38,616 | 67,101 | 142,228 | …
Not stated^3^ | 19,728 | 960 | 2,121 | 4,402 | 12,245 | …
Male | 495,122 | 52,511 | 73,486 | 114,847 | 254,278 | …
Less than high school diploma or GED | 92,902 | 10,052 | 14,481 | 21,380 | 46,989 | …
High school diploma or GED | 235,132 | 26,933 | 34,884 | 52,868 | 120,447 | …
Some college or collegiate degree | 152,863 | 14,826 | 22,634 | 37,459 | 77,944 | …
Not stated^3^ | 14,225 | 700 | 1,487 | 3,140 | 8,898 | …
Female | 291,677 | 21,858 | 38,119 | 68,437 | 163,263 | …
Less than high school diploma or GED | 44,369 | 3,523 | 5,997 | 10,264 | 24,585 | …
High school diploma or GED | 123,568 | 9,746 | 15,506 | 27,269 | 71,047 | …
Some college or collegiate degree | 118,237 | 8,329 | 15,982 | 29,642 | 64,284 | …
Not stated^3^ | 5,503 | 260 | 634 | 1,262 | 3,347 | …
| Rate
Both sexes^3^ | 457.7 | 164.4 | 253.4 | 452.8 | 991.1 | 405.6
Less than high school diploma or GED | 818.6 | 412.9 | 472.4 | 705.3 | 1,536.3 | 695.7
High school diploma or GED | 839.6 | 334.3 | 510.7 | 820.2 | 1,580.9 | 724.4
Some college or collegiate degree | 241.2 | 74.8 | 129.4 | 255.9 | 560.9 | 220.3
Male^3^ | 574.1 | 228.0 | 330.1 | 565.7 | 1,231.0 | 515.6
Less than high school diploma or GED | 987.3 | 515.3 | 584.1 | 859.6 | 1,885.3 | 855.8
High school diploma or GED | 987.0 | 420.1 | 612.4 | 976.2 | 1,911.9 | 874.5
Some college or collegiate degree | 288.3 | 101.1 | 160.7 | 302.1 | 657.0 | 265.0
Female^3^ | 340.6 | 98.4 | 175.0 | 339.2 | 760.4 | 295.8
Less than high school diploma or GED | 603.0 | 263.5 | 323.2 | 513.4 | 1,134.8 | 493.0
High school diploma or GED | 653.8 | 213.7 | 371.8 | 626.1 | 1,222.2 | 539.1
Some college or collegiate degree | 199.1 | 51.1 | 101.4 | 214.5 | 476.5 | 180.5

… Category not applicable.

^1^Excludes data for age not stated.

^2^Calculated based on ages 25–64. For method of computation, see Technical Notes.

^3^Includes deaths with education not stated.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 15 Number of deaths and death rate by age and age-adjusted death rate for injury at work for age 15 and older, by Hispanic origin and race and sex: United States, 2022

[Rates are per 100,000 population in specified group; age-adjusted rates are per 100,000 U.S. standard population; see Technical Notes in this report. Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards. Data for Hispanic origin should be interpreted with caution because of inconsistencies between reporting Hispanic origin on death certificates and on censuses and surveys, although misclassification is very minor; see Technical Notes. For a discussion of injury at work, see Technical Notes]

Hispanic origin and race and sex | Age group | | | | | | | Age-adjusted rate^2^
Hispanic origin and race and sex | 15 and older^1^ | 15–24 | 25–34 | 35–44 | 45–54 | 55–64 | 65 and older | Age-adjusted rate^2^
| Number
Total^3^, both sexes | 4,987 | 391 | 821 | 943 | 1,011 | 1,057 | 764 | …
Male | 4,517 | 342 | 742 | 861 | 925 | 976 | 671 | …
Female | 470 | 49 | 79 | 82 | 86 | 81 | 93 | …
Hispanic^4^ | 1,075 | 140 | 215 | 256 | 228 | 181 | 55 | …
Male | 1,015 | 122 | 211 | 242 | 217 | 173 | 50 | …
Female | 60 | 18 | 4 | 14 | 11 | 8 | 5 | …
Non-Hispanic, single race^5^: | | | | | | | | …
Black, both sexes | 657 | 54 | 120 | 128 | 155 | 124 | 76 | …
Male | 583 | 48 | 102 | 114 | 137 | 115 | 67 | …
Female | 74 | 6 | 18 | 14 | 18 | 9 | 9 | …
White, both sexes | 3,022 | 180 | 429 | 522 | 591 | 701 | 599 | …
Male | 2,709 | 158 | 378 | 472 | 536 | 640 | 525 | …
Female | 313 | 22 | 51 | 50 | 55 | 61 | 74 | …
| Rate
Total^3^, both sexes | 1.8 | 0.9 | 1.8 | 2.2 | 2.5 | 2.5 | 1.3 | 1.8
Male | 3.3 | 1.5 | 3.2 | 3.9 | 4.6 | 4.7 | 2.6 | 3.4
Female | 0.3 | 0.2 | 0.4 | 0.4 | 0.4 | 0.4 | 0.3 | 0.3
Hispanic^4^ | 2.2 | 1.3 | 2.2 | 2.8 | 3.0 | 3.2 | 1.0 | 2.2
Male | 4.2 | 2.2 | 4.2 | 5.1 | 5.5 | 6.1 | 2.1 | 4.1
Female | 0.3 | * | * | * | * | * | * | 0.2
Non-Hispanic, single race^5^:
Black, both sexes | 1.9 | 0.9 | 1.8 | 2.3 | 3.1 | 2.5 | 1.4 | 2.0
Male | 3.6 | 1.6 | 3.1 | 4.2 | 5.7 | 5.0 | 3.0 | 3.7
Female | 0.4 | * | * | * | * | * | * | 0.4
White, both sexes | 1.8 | 0.8 | 1.8 | 2.1 | 2.5 | 2.5 | 1.4 | 1.8
Male | 3.3 | 1.3 | 3.0 | 3.8 | 4.4 | 4.5 | 2.7 | 3.2
Female | 0.4 | 0.2 | 0.4 | 0.4 | 0.5 | 0.4 | 0.3 | 0.4

… Category not applicable.

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

^1^Excludes figures for age not stated.

^2^Calculated based on age 15 and older. For method of computation, see Technical Notes.

^3^Includes race and origin groups not shown separately; see Technical Notes.

^4^Includes persons of Hispanic origin of any race; see Technical Notes.

^5^Only one race was reported on the death certificate.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 16 Number of deaths, death rate, and age-adjusted death rate for injury at work for age 15 and older, by Hispanic origin and race and sex: United States, 1997–2022

[Excludes data for age not stated. Data for specified race and Hispanic-origin groups other than non-Hispanic White and non-Hispanic Black should be interpreted with caution because of inconsistencies between reporting Hispanic origin on death certificates and on censuses and surveys, although misclassification is very minor; see Technical Notes in this report. For a discussion of injury at work, see Technical Notes]

Hispanic origin and race and year | Number | | | Crude death rate^1^ | | | Age-adjusted death rate^2^
Hispanic origin and race and year | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All origins and races^3^
2022 | 4,987 | 4,517 | 470 | 1.8 | 3.3 | 0.3 | 1.8 | 3.4 | 0.3
2021 | 4,840 | 4,389 | 451 | 1.8 | 3.3 | 0.3 | 1.8 | 3.3 | 0.3
2020 | 4,321 | 3,921 | 400 | 1.6 | 3.0 | 0.3 | 1.6 | 3.0 | 0.3
2019 | 4,743 | 4,321 | 422 | 1.8 | 3.3 | 0.3 | 1.8 | 3.3 | 0.3
2018 | 4,560 | 4,179 | 381 | 1.7 | 3.2 | 0.3 | 1.7 | 3.2 | 0.3
2017 | 4,573 | 4,143 | 430 | 1.7 | 3.2 | 0.3 | 1.7 | 3.1 | 0.3
2016 | 4,621 | 4,169 | 452 | 1.8 | 3.3 | 0.3 | 1.7 | 3.2 | 0.3
2015^4^ | 4,185 | 3,816 | 369 | 1.6 | 3.0 | 0.3 | 1.6 | 3.0 | 0.3
2014 | 4,348 | 3,916 | 432 | 1.7 | 3.1 | 0.3 | 1.7 | 3.1 | 0.3
2013 | 4,268 | 3,882 | 386 | 1.7 | 3.1 | 0.3 | 1.7 | 3.1 | 0.3
2012 | 4,106 | 3,743 | 363 | 1.6 | 3.0 | 0.3 | 1.6 | 3.0 | 0.3
2011 | 4,097 | 3,736 | 361 | 1.6 | 3.1 | 0.3 | 1.6 | 3.0 | 0.3
2010 | 4,157 | 3,829 | 328 | 1.7 | 3.2 | 0.3 | 1.7 | 3.1 | 0.3
2009 | 3,919 | 3,601 | 318 | 1.6 | 3.0 | 0.3 | 1.6 | 3.0 | 0.3
2008 | 4,690 | 4,317 | 373 | 1.9 | 3.6 | 0.3 | 1.9 | 3.6 | 0.3
2007 | 5,025 | 4,606 | 419 | 2.1 | 3.9 | 0.3 | 2.1 | 3.9 | 0.3
2006 | 5,298 | 4,869 | 429 | 2.2 | 4.2 | 0.4 | 2.2 | 4.2 | 0.3
2005 | 5,113 | 4,670 | 443 | 2.2 | 4.1 | 0.4 | 2.2 | 4.1 | 0.4
2004 | 5,157 | 4,729 | 428 | 2.2 | 4.2 | 0.4 | 2.2 | 4.2 | 0.4
2003 | 5,025 | 4,609 | 416 | 2.2 | 4.1 | 0.4 | 2.2 | 4.1 | 0.3
2002 | 5,305 | 4,859 | 446 | 2.3 | 4.4 | 0.4 | 2.4 | 4.4 | 0.4
2001^5^ | 8,303 | 7,181 | 1,122 | 3.7 | 6.6 | 1.0 | 3.7 | 6.6 | 1.0
2000 | 5,430 | 4,969 | 461 | 2.5 | 4.6 | 0.4 | 2.5 | 4.6 | 0.4
1999 | 5,651 | 5,152 | 499 | 2.6 | 4.9 | 0.4 | 2.6 | 4.9 | 0.4
1998 | 5,543 | 5,036 | 507 | 2.6 | 4.8 | 0.5 | 2.6 | 4.8 | 0.5
1997 | 5,666 | 5,144 | 522 | 2.7 | 5.0 | 0.5 | 2.6 | 5.0 | 0.5
Hispanic^6^
2022 | 1,075 | 1,015 | 60 | 2.2 | 4.2 | 0.3 | 2.2 | 4.1 | 0.2
2021 | 1,041 | 996 | 45 | 2.2 | 4.2 | 0.2 | 2.2 | 4.2 | 0.2
2020 | 950 | 903 | 47 | 2.1 | 3.9 | 0.2 | 2.1 | 4.0 | 0.2
2019 | 959 | 907 | 52 | 2.1 | 4.0 | 0.2 | 2.2 | 4.1 | 0.2
2018 | 827 | 786 | 41 | 1.9 | 3.5 | 0.2 | 1.9 | 3.6 | 0.2
2017 | 796 | 755 | 41 | 1.8 | 3.5 | 0.2 | 1.9 | 3.6 | 0.2
2016 | 795 | 753 | 42 | 1.9 | 3.6 | 0.2 | 1.9 | 3.7 | 0.2
2015^4^ | 771 | 738 | 33 | 1.9 | 3.5 | 0.2 | 1.9 | 3.7 | 0.2
2014 | 718 | 681 | 37 | 1.8 | 3.4 | 0.2 | 1.9 | 3.6 | 0.2
2013 | 735 | 698 | 37 | 1.9 | 3.5 | 0.2 | 1.9 | 3.7 | 0.2
2012 | 682 | 649 | 33 | 1.8 | 3.4 | 0.2 | 1.8 | 3.5 | 0.2
2011 | 630 | 590 | 40 | 1.7 | 3.1 | 0.2 | 1.7 | 3.2 | 0.2
2010 | 604 | 572 | 32 | 1.7 | 3.1 | 0.2 | 1.7 | 3.3 | 0.2
2009 | 619 | 583 | 36 | 1.8 | 3.3 | 0.2 | 1.8 | 3.5 | 0.2
2008 | 680 | 643 | 37 | 2.0 | 3.7 | 0.2 | 2.0 | 3.8 | 0.2
2007 | 794 | 761 | 33 | 2.4 | 4.6 | 0.2 | 2.4 | 4.5 | 0.2
2006 | 856 | 820 | 36 | 2.7 | 5.1 | 0.2 | 2.7 | 5.1 | 0.2
2005 | 761 | 718 | 43 | 2.5 | 4.6 | 0.3 | 2.5 | 4.6 | 0.3
2004 | 735 | 702 | 33 | 2.5 | 4.7 | 0.2 | 2.5 | 4.7 | 0.2
2003 | 671 | 635 | 36 | 2.4 | 4.4 | 0.3 | 2.3 | 4.4 | 0.2
2002 | 757 | 710 | 47 | 2.8 | 5.1 | 0.4 | 2.8 | 5.2 | 0.4
2001^5^ | 1,049 | 916 | 133 | 4.0 | 6.8 | 1.0 | 4.1 | 7.1 | 1.0
2000 | 718 | 684 | 34 | 2.9 | 5.3 | 0.3 | 2.8 | 5.4 | 0.3
1999 | 597 | 566 | 31 | 2.5 | 4.6 | 0.3 | 2.5 | 4.8 | 0.3
1998 | 610 | 584 | 26 | 2.7 | 5.0 | 0.2 | 2.7 | 5.1 | 0.2
1997 | 571 | 531 | 40 | 2.6 | 4.8 | 0.4 | 2.7 | 5.0 | 0.4
Non-Hispanic, single race^7^
American Indian and Alaska Native:
2022 | 37 | 29 | 8 | 1.9 | 3.0 | * | 1.9 | 3.0 | *
2021 | 37 | 31 | 6 | 1.9 | 3.2 | * | 1.9 | 3.2 | *
2020 | 31 | 25 | 6 | 1.6 | 2.6 | * | 1.6 | 2.5 | *
2019 | 30 | 26 | 4 | 1.6 | 2.8 | * | 1.6 | 2.8 | *
2018 | 40 | 36 | 4 | 2.1 | 3.9 | * | 2.1 | 3.9 | *
Asian:
2022 | 130 | 117 | 13 | 0.8 | 1.5 | * | 0.7 | 1.4 | *
2021 | 140 | 120 | 20 | 0.9 | 1.5 | 0.2 | 0.8 | 1.5 | 0.2
2020 | 118 | 104 | 14 | 0.7 | 1.4 | * | 0.7 | 1.3 | *
2019 | 154 | 139 | 15 | 1.0 | 1.9 | * | 0.9 | 1.8 | *
2018 | 114 | 103 | 11 | 0.7 | 1.4 | * | 0.7 | 1.4 | *
Black:
2022 | 657 | 583 | 74 | 1.9 | 3.6 | 0.4 | 2.0 | 3.7 | 0.4
2021 | 619 | 545 | 74 | 1.8 | 3.4 | 0.4 | 1.9 | 3.4 | 0.4
2020 | 521 | 469 | 52 | 1.6 | 3.0 | 0.3 | 1.6 | 3.0 | 0.3
2019 | 572 | 513 | 59 | 1.7 | 3.3 | 0.3 | 1.7 | 3.4 | 0.3
2018 | 520 | 475 | 45 | 1.6 | 3.1 | 0.3 | 1.6 | 3.1 | 0.3
Native Hawaiian or Other Pacific Islander:
2022 | 6 | 6 | – | * | * | * | * | * | *
2021 | 12 | 11 | 1 | * | * | * | * | * | *
2020 | 6 | 6 | – | * | * | * | * | * | *
2019 | 13 | 12 | 1 | * | * | * | * | * | *
2018 | 11 | 11 | – | * | * | * | * | * | *
White:
2022 | 3,022 | 2,709 | 313 | 1.8 | 3.3 | 0.4 | 1.8 | 3.2 | 0.4
2021 | 2,941 | 2,646 | 295 | 1.8 | 3.2 | 0.3 | 1.7 | 3.2 | 0.4
2020 | 2,655 | 2,386 | 269 | 1.6 | 2.9 | 0.3 | 1.6 | 2.9 | 0.3
2019 | 2,975 | 2,687 | 288 | 1.8 | 3.3 | 0.3 | 1.8 | 3.2 | 0.3
2018 | 3,006 | 2,728 | 278 | 1.8 | 3.3 | 0.3 | 1.8 | 3.3 | 0.3

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

– Quantity zero.

^1^Rates are on an annual basis per 100,000 population in specified group; see Technical Notes.

^2^Age-adjusted rates are per 100,000 U.S. standard population. For method of computation, see Technical Notes.

^3^Includes races and origins not shown separately; see Technical Notes.

^4^Excludes data for Tennessee; see Supplemental Technical Notes from “Deaths: Final Data for 2015,” National Vital Statistics Reports, vol 66, no 6.

^5^Data include September 11, 2001, terrorism-related deaths for which death certificates were filed as of October 24, 2002; see Technical Notes from “Deaths: Final Data for 2001,” National Vital Statistics Reports, vol 52, no 3.

^6^Includes people of Hispanic origin of any race. The Hispanic-origin category is consistent with 1997 Office of Management and Budget (OMB) standards; see Technical Notes.

^7^Only one race was reported on the death certificate. Race and Hispanic-origin categories are consistent with 1997 OMB standards; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 17 Number of deaths, death rate, and age-adjusted death rate for major causes of death: United States, each state, Puerto Rico, U.S. Virgin Islands, Guam, American Samoa, and Northern Marianas, 2022

[Rates per 100,000 population; age-adjusted rates per 100,000 U.S. standard population; see Technical Notes in this report. Codes in parentheses after causes of death are categories of the International Classification of Diseases, 10th Revision (ICD–10). An asterisk (*) preceding a cause-of-death code indicates that the code is not included in ICD–10; see Technical Notes]

Area | All causes | | | Septicemia (A40–A41) | | | Human immunodeficiency virus (HIV) disease (B20–B24) | | | Malignant neoplasms(C00–C97)
Area | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^
United States^2^ | 3,279,857 | 984.1 | 798.8 | 42,261 | 12.7 | 10.1 | 4,941 | 1.5 | 1.3 | 608,371 | 182.5 | 142.3
Alabama | 62,294 | 1,227.6 | 989.1 | 1,168 | 23.0 | 17.9 | 83 | 1.6 | 1.5 | 10,328 | 203.5 | 154.4
Alaska | 5,719 | 779.6 | 821.3 | 72 | 9.8 | 11.0 | 3 | * | * | 1,076 | 146.7 | 145.3
Arizona | 74,082 | 1,006.7 | 784.6 | 519 | 7.1 | 5.5 | 103 | 1.4 | 1.4 | 13,171 | 179.0 | 132.9
Arkansas | 37,855 | 1,242.9 | 999.7 | 646 | 21.2 | 16.9 | 27 | 0.9 | 0.8 | 6,638 | 218.0 | 168.1
California | 313,161 | 802.4 | 686.0 | 1,852 | 4.7 | 4.0 | 558 | 1.4 | 1.3 | 60,449 | 154.9 | 129.8
Colorado | 46,787 | 801.2 | 736.3 | 503 | 8.6 | 7.7 | 39 | 0.7 | 0.6 | 8,324 | 142.5 | 124.5
Connecticut | 34,583 | 953.7 | 716.8 | 465 | 12.8 | 9.4 | 43 | 1.2 | 0.9 | 6,658 | 183.6 | 133.6
Delaware | 11,351 | 1,114.6 | 829.1 | 130 | 12.8 | 9.1 | 14 | * | * | 2,373 | 233.0 | 160.7
District of Columbia | 5,385 | 801.6 | 789.6 | 79 | 11.8 | 11.3 | 43 | 6.4 | 6.2 | 963 | 143.3 | 141.8
Florida | 239,119 | 1,074.9 | 714.7 | 2,900 | 13.0 | 8.5 | 640 | 2.9 | 2.5 | 47,035 | 211.4 | 135.8
Georgia | 102,342 | 937.8 | 871.6 | 1,786 | 16.4 | 14.7 | 312 | 2.9 | 2.6 | 18,302 | 167.7 | 147.0
Hawaii | 13,228 | 918.5 | 615.9 | 141 | 9.8 | 6.6 | 12 | * | * | 2,614 | 181.5 | 122.4
Idaho | 17,162 | 885.1 | 771.4 | 122 | 6.3 | 5.4 | 3 | * | * | 3,137 | 161.8 | 133.7
Illinois | 122,963 | 977.3 | 784.9 | 1,822 | 14.5 | 11.4 | 122 | 1.0 | 0.8 | 23,456 | 186.4 | 145.1
Indiana | 75,368 | 1,103.0 | 923.4 | 839 | 12.3 | 10.1 | 68 | 1.0 | 0.9 | 13,873 | 203.0 | 162.5
Iowa | 33,973 | 1,061.5 | 798.0 | 376 | 11.7 | 8.9 | 15 | * | * | 6,285 | 196.4 | 146.1
Kansas | 31,551 | 1,074.2 | 873.2 | 341 | 11.6 | 9.4 | 22 | 0.7 | 0.6 | 5,512 | 187.7 | 148.8
Kentucky | 57,053 | 1,264.4 | 1,043.8 | 1,015 | 22.5 | 18.1 | 51 | 1.1 | 1.0 | 10,300 | 228.3 | 177.3
Louisiana | 52,339 | 1,140.2 | 974.7 | 1,108 | 24.1 | 19.8 | 124 | 2.7 | 2.6 | 9,193 | 200.3 | 160.3
Maine | 17,364 | 1,253.4 | 844.3 | 51 | 3.7 | 2.7 | 12 | * | * | 3,428 | 247.4 | 154.3
Maryland | 56,456 | 915.8 | 746.5 | 986 | 16.0 | 12.7 | 149 | 2.4 | 2.0 | 10,819 | 175.5 | 136.8
Massachusetts | 63,366 | 907.6 | 693.5 | 939 | 13.4 | 10.1 | 57 | 0.8 | 0.6 | 12,436 | 178.1 | 132.2
Michigan | 110,499 | 1,101.2 | 855.4 | 1,326 | 13.2 | 9.9 | 89 | 0.9 | 0.8 | 21,032 | 209.6 | 154.4
Minnesota | 51,222 | 895.9 | 710.3 | 502 | 8.8 | 6.9 | 30 | 0.5 | 0.4 | 10,284 | 179.9 | 139.0
Mississippi | 37,803 | 1,285.8 | 1,073.3 | 393 | 13.4 | 10.9 | 76 | 2.6 | 2.5 | 6,665 | 226.7 | 178.4
Missouri | 71,851 | 1,163.0 | 916.7 | 1,025 | 16.6 | 12.8 | 51 | 0.8 | 0.8 | 13,071 | 211.6 | 159.6
Montana | 11,684 | 1,040.6 | 795.9 | 116 | 10.3 | 7.5 | 3 | * | * | 2,234 | 199.0 | 142.2
Nebraska | 18,615 | 945.9 | 773.5 | 226 | 11.5 | 9.2 | 11 | * | * | 3,490 | 177.3 | 142.2
Nevada | 30,960 | 974.3 | 842.1 | 272 | 8.6 | 7.2 | 49 | 1.5 | 1.4 | 5,420 | 170.6 | 138.9
New Hampshire | 14,515 | 1,040.3 | 749.7 | 173 | 12.4 | 8.8 | 6 | * | * | 2,908 | 208.4 | 141.4
New Jersey | 81,490 | 879.9 | 683.6 | 2,029 | 21.9 | 16.8 | 148 | 1.6 | 1.3 | 15,330 | 165.5 | 125.3
New Mexico | 23,655 | 1,119.3 | 901.4 | 283 | 13.4 | 10.6 | 19 | * | * | 3,646 | 172.5 | 127.5
New York | 173,944 | 884.0 | 664.5 | 2,512 | 12.8 | 9.5 | 364 | 1.8 | 1.6 | 32,655 | 166.0 | 122.4
North Carolina | 112,923 | 1,055.5 | 877.1 | 1,500 | 14.0 | 11.4 | 170 | 1.6 | 1.4 | 20,409 | 190.8 | 149.0
North Dakota | 7,041 | 903.5 | 739.2 | 89 | 11.4 | 9.3 | 3 | * | * | 1,214 | 155.8 | 128.4
Ohio | 138,209 | 1,175.6 | 917.2 | 1,982 | 16.9 | 12.8 | 112 | 1.0 | 0.9 | 24,616 | 209.4 | 155.5
Oklahoma | 47,976 | 1,193.5 | 1,025.6 | 364 | 9.1 | 7.8 | 63 | 1.6 | 1.6 | 8,378 | 208.4 | 171.6
Oregon | 44,598 | 1,051.8 | 811.3 | 323 | 7.6 | 5.8 | 48 | 1.1 | 1.0 | 8,485 | 200.1 | 147.0
Pennsylvania | 147,181 | 1,134.6 | 818.2 | 2,546 | 19.6 | 13.8 | 141 | 1.1 | 1.0 | 27,648 | 213.1 | 148.7
Rhode Island | 10,704 | 978.7 | 714.0 | 75 | 6.9 | 4.9 | 11 | * | * | 2,091 | 191.2 | 136.5
South Carolina | 61,052 | 1,155.7 | 918.8 | 908 | 17.2 | 13.2 | 126 | 2.4 | 2.1 | 11,015 | 208.5 | 153.2
South Dakota | 9,016 | 991.0 | 801.0 | 105 | 11.5 | 9.4 | 5 | * | * | 1,705 | 187.4 | 144.7
Tennessee | 84,989 | 1,205.3 | 1,009.2 | 968 | 13.7 | 11.1 | 107 | 1.5 | 1.4 | 14,625 | 207.4 | 162.3
Texas | 241,441 | 804.0 | 816.9 | 3,586 | 11.9 | 11.9 | 556 | 1.9 | 1.8 | 43,403 | 144.5 | 140.8
Utah | 21,886 | 647.4 | 755.0 | 270 | 8.0 | 9.3 | 22 | 0.7 | 0.6 | 3,501 | 103.6 | 116.1
Vermont | 6,971 | 1,077.3 | 757.6 | 38 | 5.9 | 4.1 | 3 | * | * | 1,485 | 229.5 | 150.2
Virginia | 82,935 | 955.1 | 794.1 | 1,072 | 12.3 | 9.9 | 111 | 1.3 | 1.0 | 15,842 | 182.4 | 144.8
Washington | 69,194 | 888.7 | 757.9 | 720 | 9.2 | 7.8 | 56 | 0.7 | 0.6 | 13,432 | 172.5 | 140.9
West Virginia | 27,507 | 1,549.6 | 1,115.6 | 292 | 16.4 | 11.4 | 21 | 1.2 | 1.0 | 4,679 | 263.6 | 176.3
Wisconsin | 60,590 | 1,028.2 | 791.5 | 638 | 10.8 | 8.1 | 37 | 0.6 | 0.6 | 11,654 | 197.8 | 145.3
Wyoming | 5,905 | 1,015.7 | 826.8 | 68 | 11.7 | 9.0 | 3 | * | * | 1,084 | 186.5 | 143.0
Puerto Rico | 35,111 | 1,089.8 | 650.1 | 703 | 21.8 | 12.2 | 129 | 4.0 | 3.1 | 5,375 | 166.8 | 99.0
U.S. Virgin Islands | 731 | 693.5 | 531.2 | 14 | * | * | 2 | * | * | 113 | 107.2 | 71.4
Guam | 1,235 | 730.4 | 965.6 | 54 | 31.9 | 43.5 | – | * | * | 200 | 118.3 | 148.5
American Samoa | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 271 | 526.5 | 839.3 | 6 | * | * | – | * | * | 48 | 93.2 | 136.0
Area | Diabetes mellitus (E10–E14) | | | Parkinson disease (G20–G21) | | | Alzheimer disease (G30) | | | Diseases of heart (I00–I09,I11,I13,I20–I51)
Area | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^
United States^2^ | 101,209 | 30.4 | 24.1 | 39,915 | 12.0 | 9.5 | 120,122 | 36.0 | 28.9 | 702,880 | 210.9 | 167.2
Alabama | 1,645 | 32.4 | 25.4 | 696 | 13.7 | 10.7 | 2,655 | 52.3 | 42.2 | 14,958 | 294.8 | 234.2
Alaska | 184 | 25.1 | 25.6 | 62 | 8.5 | 10.9 | 178 | 24.3 | 33.1 | 1,013 | 138.1 | 145.7
Arizona | 2,423 | 32.9 | 25.1 | 1,007 | 13.7 | 9.9 | 2,823 | 38.4 | 28.4 | 14,593 | 198.3 | 148.5
Arkansas | 1,397 | 45.9 | 36.0 | 382 | 12.5 | 9.8 | 1,577 | 51.8 | 41.0 | 8,664 | 284.5 | 224.1
California | 11,618 | 29.8 | 25.0 | 4,289 | 11.0 | 9.4 | 17,363 | 44.5 | 37.5 | 66,340 | 170.0 | 142.4
Colorado | 1,215 | 20.8 | 18.5 | 665 | 11.4 | 10.7 | 1,871 | 32.0 | 31.4 | 8,389 | 143.6 | 131.4
Connecticut | 746 | 20.6 | 15.2 | 431 | 11.9 | 8.7 | 1,080 | 29.8 | 21.5 | 6,899 | 190.3 | 137.8
Delaware | 361 | 35.4 | 25.1 | 131 | 12.9 | 9.0 | 435 | 42.7 | 31.5 | 2,220 | 218.0 | 156.8
District of Columbia | 123 | 18.3 | 18.2 | 45 | 6.7 | 6.9 | 70 | 10.4 | 10.2 | 1,239 | 184.4 | 182.6
Florida | 7,549 | 33.9 | 22.3 | 3,169 | 14.2 | 8.5 | 6,397 | 28.8 | 17.0 | 49,877 | 224.2 | 140.9
Georgia | 2,693 | 24.7 | 21.9 | 1,168 | 10.7 | 10.3 | 4,219 | 38.7 | 39.3 | 21,728 | 199.1 | 183.9
Hawaii | 363 | 25.2 | 17.2 | 186 | 12.9 | 8.0 | 575 | 39.9 | 22.0 | 2,862 | 198.7 | 128.4
Idaho | 473 | 24.4 | 20.5 | 243 | 12.5 | 10.8 | 848 | 43.7 | 39.5 | 3,491 | 180.0 | 156.3
Illinois | 3,463 | 27.5 | 21.8 | 1,504 | 12.0 | 9.4 | 4,111 | 32.7 | 25.6 | 26,781 | 212.9 | 166.6
Indiana | 2,493 | 36.5 | 29.8 | 904 | 13.2 | 10.9 | 2,259 | 33.1 | 27.8 | 15,385 | 225.2 | 185.0
Iowa | 1,009 | 31.5 | 24.0 | 466 | 14.6 | 10.7 | 1,348 | 42.1 | 29.4 | 7,786 | 243.3 | 176.8
Kansas | 963 | 32.8 | 26.2 | 423 | 14.4 | 11.5 | 944 | 32.1 | 25.2 | 6,440 | 219.3 | 173.2
Kentucky | 1,668 | 37.0 | 29.4 | 548 | 12.1 | 10.0 | 1,509 | 33.4 | 28.4 | 11,654 | 258.3 | 208.6
Louisiana | 1,655 | 36.1 | 29.9 | 540 | 11.8 | 9.9 | 2,094 | 45.6 | 40.0 | 12,284 | 267.6 | 224.0
Maine | 603 | 43.5 | 28.2 | 228 | 16.5 | 10.3 | 543 | 39.2 | 24.9 | 3,592 | 259.3 | 167.1
Maryland | 1,796 | 29.1 | 23.1 | 627 | 10.2 | 8.2 | 1,186 | 19.2 | 15.5 | 12,086 | 196.1 | 155.8
Massachusetts | 1,503 | 21.5 | 16.1 | 747 | 10.7 | 8.0 | 1,596 | 22.9 | 17.0 | 12,427 | 178.0 | 132.3
Michigan | 3,418 | 34.1 | 25.6 | 1,331 | 13.3 | 10.1 | 4,200 | 41.9 | 32.4 | 27,266 | 271.7 | 206.3
Minnesota | 1,514 | 26.5 | 20.5 | 805 | 14.1 | 10.9 | 2,358 | 41.2 | 31.6 | 9,175 | 160.5 | 124.1
Mississippi | 1,256 | 42.7 | 34.7 | 367 | 12.5 | 10.2 | 1,679 | 57.1 | 48.5 | 8,858 | 301.3 | 248.0
Missouri | 1,878 | 30.4 | 23.5 | 818 | 13.2 | 10.1 | 2,620 | 42.4 | 32.5 | 16,143 | 261.3 | 199.8
Montana | 329 | 29.3 | 22.0 | 155 | 13.8 | 10.2 | 338 | 30.1 | 22.5 | 2,539 | 226.1 | 165.9
Nebraska | 539 | 27.4 | 22.1 | 275 | 14.0 | 11.4 | 746 | 37.9 | 30.0 | 3,804 | 193.3 | 154.3
Nevada | 898 | 28.3 | 23.4 | 267 | 8.4 | 7.3 | 863 | 27.2 | 25.3 | 7,337 | 230.9 | 196.8
New Hampshire | 454 | 32.5 | 22.3 | 218 | 15.6 | 11.1 | 462 | 33.1 | 23.9 | 2,951 | 211.5 | 147.5
New Jersey | 2,099 | 22.7 | 17.3 | 939 | 10.1 | 7.8 | 2,320 | 25.0 | 18.8 | 18,707 | 202.0 | 152.8
New Mexico | 860 | 40.7 | 31.2 | 249 | 11.8 | 8.7 | 733 | 34.7 | 26.6 | 4,369 | 206.7 | 156.8
New York | 4,788 | 24.3 | 18.2 | 1,751 | 8.9 | 6.5 | 3,265 | 16.6 | 11.7 | 43,237 | 219.7 | 159.2
North Carolina | 3,834 | 35.8 | 28.8 | 1,278 | 11.9 | 9.8 | 4,272 | 39.9 | 33.9 | 21,763 | 203.4 | 165.8
North Dakota | 234 | 30.0 | 25.1 | 79 | 10.1 | 8.1 | 336 | 43.1 | 31.6 | 1,538 | 197.4 | 155.0
Ohio | 4,268 | 36.3 | 27.6 | 1,565 | 13.3 | 10.1 | 4,953 | 42.1 | 32.3 | 30,041 | 255.5 | 193.9
Oklahoma | 1,586 | 39.5 | 33.8 | 484 | 12.0 | 10.2 | 1,613 | 40.1 | 34.7 | 12,268 | 305.2 | 257.1
Oregon | 1,454 | 34.3 | 25.4 | 626 | 14.8 | 11.0 | 2,030 | 47.9 | 37.0 | 8,152 | 192.3 | 145.4
Pennsylvania | 4,124 | 31.8 | 22.6 | 1,725 | 13.3 | 9.2 | 4,011 | 30.9 | 20.9 | 32,522 | 250.7 | 173.4
Rhode Island | 293 | 26.8 | 18.9 | 124 | 11.3 | 8.1 | 475 | 43.4 | 29.8 | 2,369 | 216.6 | 152.6
South Carolina | 1,784 | 33.8 | 25.8 | 684 | 12.9 | 9.9 | 2,429 | 46.0 | 37.4 | 12,038 | 227.9 | 177.7
South Dakota | 339 | 37.3 | 29.4 | 100 | 11.0 | 8.8 | 435 | 47.8 | 36.5 | 1,850 | 203.3 | 158.2
Tennessee | 2,722 | 38.6 | 31.2 | 957 | 13.6 | 11.2 | 2,933 | 41.6 | 36.0 | 18,727 | 265.6 | 218.3
Texas | 7,853 | 26.2 | 25.6 | 3,091 | 10.3 | 11.1 | 10,427 | 34.7 | 38.8 | 50,672 | 168.7 | 172.3
Utah | 763 | 22.6 | 25.4 | 343 | 10.1 | 12.4 | 1,057 | 31.3 | 39.8 | 4,460 | 131.9 | 159.4
Vermont | 179 | 27.7 | 18.9 | 105 | 16.2 | 10.9 | 329 | 50.8 | 34.5 | 1,589 | 245.6 | 165.1
Virginia | 2,875 | 33.1 | 26.9 | 1,067 | 12.3 | 10.2 | 2,506 | 28.9 | 24.4 | 16,902 | 194.6 | 159.2
Washington | 2,199 | 28.2 | 23.3 | 928 | 11.9 | 10.2 | 3,695 | 47.5 | 41.6 | 13,218 | 169.8 | 142.7
West Virginia | 1,056 | 59.5 | 41.1 | 282 | 15.9 | 10.7 | 755 | 42.5 | 29.5 | 5,399 | 304.1 | 209.5
Wisconsin | 1,490 | 25.3 | 19.1 | 780 | 13.2 | 10.0 | 2,361 | 40.1 | 30.3 | 13,128 | 222.8 | 166.6
Wyoming | 180 | 31.0 | 24.5 | 61 | 10.5 | 8.5 | 240 | 41.3 | 34.7 | 1,150 | 197.8 | 157.1
Puerto Rico | 3,079 | 95.6 | 54.7 | 262 | 8.1 | 4.2 | 3,004 | 93.2 | 45.7 | 6,005 | 186.4 | 102.4
U.S. Virgin Islands | 24 | 22.8 | 18.6 | 2 | * | * | 50 | 47.4 | 37.0 | 179 | 169.8 | 120.5
Guam | 15 | * | * | 5 | * | * | 13 | * | * | 398 | 235.4 | 313.4
American Samoa | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 24 | 46.6 | 65.3 | 1 | * | * | - | * | * | 46 | 89.4 | 100.2
Area | Essential hypertension and hypertensive renal disease (I10,I12,I15) | | | Cerebrovascular diseases (I60–I69) | | | Influenza and pneumonia (J09–J18) | | | Chronic lower respiratory diseases (J40–J47)
Area | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^
United States^2^ | 43,293 | 13.0 | 10.3 | 165,393 | 49.6 | 39.5 | 47,052 | 14.1 | 11.3 | 147,382 | 44.2 | 34.3
Alabama | 849 | 16.7 | 13.2 | 3,291 | 64.9 | 51.1 | 957 | 18.9 | 14.9 | 3,157 | 62.2 | 46.9
Alaska | 56 | 7.6 | 8.6 | 223 | 30.4 | 35.1 | 75 | 10.2 | 10.4 | 212 | 28.9 | 30.2
Arizona | 1,109 | 15.1 | 11.3 | 3,390 | 46.1 | 34.5 | 962 | 13.1 | 10.1 | 3,577 | 48.6 | 35.1
Arkansas | 454 | 14.9 | 12.1 | 1,774 | 58.2 | 46.0 | 653 | 21.4 | 17.2 | 2,387 | 78.4 | 59.7
California | 6,727 | 17.2 | 14.4 | 18,442 | 47.3 | 39.8 | 5,308 | 13.6 | 11.5 | 11,977 | 30.7 | 25.8
Colorado | 400 | 6.8 | 6.4 | 2,098 | 35.9 | 33.8 | 469 | 8.0 | 7.3 | 2,467 | 42.2 | 38.0
Connecticut | 386 | 10.6 | 7.7 | 1,504 | 41.5 | 30.1 | 563 | 15.5 | 11.2 | 1,226 | 33.8 | 24.3
Delaware | 113 | 11.1 | 8.1 | 805 | 79.0 | 56.9 | 146 | 14.3 | 10.1 | 473 | 46.4 | 32.0
District of Columbia | 82 | 12.2 | 11.9 | 287 | 42.7 | 42.1 | 58 | 8.6 | 8.5 | 120 | 17.9 | 17.3
Florida | 3,289 | 14.8 | 9.3 | 16,385 | 73.7 | 45.1 | 2,887 | 13.0 | 8.3 | 11,172 | 50.2 | 30.6
Georgia | 1,435 | 13.1 | 12.1 | 5,110 | 46.8 | 44.0 | 1,333 | 12.2 | 11.3 | 4,782 | 43.8 | 39.6
Hawaii | 180 | 12.5 | 8.1 | 905 | 62.8 | 39.5 | 281 | 19.5 | 12.4 | 358 | 24.9 | 15.6
Idaho | 148 | 7.6 | 6.7 | 765 | 39.5 | 34.4 | 201 | 10.4 | 9.3 | 986 | 50.9 | 41.6
Illinois | 1,496 | 11.9 | 9.3 | 6,672 | 53.0 | 41.4 | 2,011 | 16.0 | 12.7 | 5,251 | 41.7 | 32.2
Indiana | 796 | 11.6 | 9.6 | 3,478 | 50.9 | 41.9 | 887 | 13.0 | 10.7 | 4,544 | 66.5 | 53.0
Iowa | 527 | 16.5 | 11.9 | 1,412 | 44.1 | 32.0 | 500 | 15.6 | 11.5 | 1,730 | 54.1 | 39.0
Kansas | 554 | 18.9 | 14.7 | 1,324 | 45.1 | 35.8 | 486 | 16.5 | 13.2 | 1,676 | 57.1 | 44.4
Kentucky | 601 | 13.3 | 10.9 | 2,366 | 52.4 | 42.9 | 888 | 19.7 | 16.1 | 3,260 | 72.2 | 55.8
Louisiana | 450 | 9.8 | 8.3 | 2,724 | 59.3 | 50.2 | 586 | 12.8 | 10.7 | 2,201 | 47.9 | 38.8
Maine | 165 | 11.9 | 7.4 | 639 | 46.1 | 29.4 | 281 | 20.3 | 13.3 | 901 | 65.0 | 40.0
Maryland | 735 | 11.9 | 9.5 | 3,360 | 54.5 | 43.8 | 708 | 11.5 | 9.3 | 1,915 | 31.1 | 24.5
Massachusetts | 769 | 11.0 | 8.1 | 2,396 | 34.3 | 25.6 | 934 | 13.4 | 10.1 | 2,378 | 34.1 | 25.0
Michigan | 1,269 | 12.6 | 9.6 | 5,802 | 57.8 | 44.2 | 1,442 | 14.4 | 11.0 | 5,292 | 52.7 | 38.5
Minnesota | 944 | 16.5 | 12.5 | 2,347 | 41.1 | 31.8 | 527 | 9.2 | 7.3 | 2,175 | 38.0 | 29.1
Mississippi | 641 | 21.8 | 18.0 | 1,943 | 66.1 | 54.2 | 761 | 25.9 | 21.1 | 2,214 | 75.3 | 59.5
Missouri | 554 | 9.0 | 6.8 | 3,153 | 51.0 | 39.1 | 1,098 | 17.8 | 13.7 | 3,809 | 61.7 | 45.9
Montana | 96 | 8.5 | 6.3 | 400 | 35.6 | 26.5 | 113 | 10.1 | 7.4 | 625 | 55.7 | 39.6
Nebraska | 430 | 21.9 | 17.2 | 867 | 44.1 | 35.1 | 288 | 14.6 | 11.9 | 929 | 47.2 | 37.4
Nevada | 468 | 14.7 | 12.8 | 1,445 | 45.5 | 40.0 | 569 | 17.9 | 15.4 | 1,618 | 50.9 | 42.8
New Hampshire | 125 | 9.0 | 6.3 | 600 | 43.0 | 30.3 | 163 | 11.7 | 8.5 | 745 | 53.4 | 36.3
New Jersey | 1,017 | 11.0 | 8.3 | 3,643 | 39.3 | 30.0 | 1,149 | 12.4 | 9.5 | 2,667 | 28.8 | 21.8
New Mexico | 181 | 8.6 | 6.6 | 1,044 | 49.4 | 38.1 | 365 | 17.3 | 13.4 | 1,113 | 52.7 | 38.6
New York | 2,836 | 14.4 | 10.3 | 6,605 | 33.6 | 24.5 | 4,065 | 20.7 | 15.1 | 6,105 | 31.0 | 22.6
North Carolina | 1,301 | 12.2 | 9.9 | 6,189 | 57.8 | 47.7 | 1,523 | 14.2 | 11.7 | 5,280 | 49.4 | 38.7
North Dakota | 87 | 11.2 | 8.2 | 330 | 42.3 | 32.8 | 125 | 16.0 | 13.0 | 305 | 39.1 | 30.7
Ohio | 1,621 | 13.8 | 10.4 | 7,202 | 61.3 | 46.5 | 1,906 | 16.2 | 12.5 | 6,807 | 57.9 | 42.6
Oklahoma | 432 | 10.7 | 9.2 | 1,884 | 46.9 | 39.5 | 656 | 16.3 | 14.0 | 3,053 | 75.9 | 62.3
Oregon | 707 | 16.7 | 12.5 | 2,630 | 62.0 | 47.1 | 370 | 8.7 | 6.7 | 2,020 | 47.6 | 34.4
Pennsylvania | 1,369 | 10.6 | 7.2 | 6,870 | 53.0 | 36.6 | 2,022 | 15.6 | 10.9 | 5,856 | 45.1 | 30.8
Rhode Island | 187 | 17.1 | 12.0 | 448 | 41.0 | 29.2 | 91 | 8.3 | 6.1 | 433 | 39.6 | 27.4
South Carolina | 728 | 13.8 | 10.6 | 3,100 | 58.7 | 45.6 | 697 | 13.2 | 10.3 | 2,851 | 54.0 | 39.7
South Dakota | 124 | 13.6 | 10.5 | 392 | 43.1 | 33.1 | 130 | 14.3 | 11.3 | 418 | 45.9 | 35.3
Tennessee | 1,043 | 14.8 | 12.3 | 3,949 | 56.0 | 46.4 | 1,330 | 18.9 | 15.6 | 4,214 | 59.8 | 47.0
Texas | 2,567 | 8.5 | 8.8 | 12,225 | 40.7 | 42.3 | 3,025 | 10.1 | 10.3 | 10,014 | 33.3 | 34.0
Utah | 216 | 6.4 | 7.6 | 959 | 28.4 | 34.6 | 266 | 7.9 | 9.3 | 894 | 26.4 | 30.3
Vermont | 69 | 10.7 | 7.2 | 261 | 40.3 | 27.1 | 71 | 11.0 | 7.3 | 291 | 45.0 | 29.6
Virginia | 991 | 11.4 | 9.4 | 4,326 | 49.8 | 41.2 | 1,068 | 12.3 | 10.0 | 3,240 | 37.3 | 29.6
Washington | 963 | 12.4 | 10.4 | 3,339 | 42.9 | 36.7 | 803 | 10.3 | 8.8 | 2,925 | 37.6 | 30.7
West Virginia | 303 | 17.1 | 11.8 | 1,117 | 62.9 | 43.4 | 535 | 30.1 | 21.5 | 1,676 | 94.4 | 61.9
Wisconsin | 657 | 11.1 | 8.4 | 2,761 | 46.9 | 35.3 | 638 | 10.8 | 8.2 | 2,709 | 46.0 | 33.7
Wyoming | 46 | 7.9 | 6.1 | 212 | 36.5 | 29.8 | 82 | 14.1 | 12.1 | 354 | 60.9 | 45.4
Puerto Rico | 688 | 21.4 | 11.6 | 1,327 | 41.2 | 22.7 | 836 | 25.9 | 14.4 | 1,034 | 32.1 | 17.0
U.S. Virgin Islands | 38 | 36.0 | 25.3 | 37 | 35.1 | 26.6 | 11 | * | * | 8 | * | *
Guam | 3 | * | * | 91 | 53.8 | 69.9 | 21 | 12.4 | 14.6 | 25 | 14.8 | 22.8
American Samoa | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 10 | * | * | 24 | 46.6 | 85.5 | 3 | * | * | 4 | * | *
Area | Chronic liver disease and cirrhosis (K70,K73–K74) | | | Nephritis, nephrotic syndrome, and nephrosis (N00–N07,N17–N19,N25–N27) | | | COVID-19 (U07.1) | | | Accidents (unintentional injuries) (V01–X59,Y85–Y86)
Area | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^
United States^2^ | 54,803 | 16.4 | 13.8 | 57,937 | 17.4 | 13.8 | 186,552 | 56.0 | 44.5 | 227,039 | 68.1 | 64.0
Alabama | 967 | 19.1 | 15.5 | 1,324 | 26.1 | 20.3 | 3,576 | 70.5 | 54.6 | 3,524 | 69.4 | 68.3
Alaska | 185 | 25.2 | 23.7 | 97 | 13.2 | 14.7 | 264 | 36.0 | 38.3 | 561 | 76.5 | 77.6
Arizona | 1,492 | 20.3 | 17.5 | 836 | 11.4 | 8.5 | 4,607 | 62.6 | 47.4 | 5,928 | 80.6 | 75.6
Arkansas | 606 | 19.9 | 16.4 | 822 | 27.0 | 21.2 | 2,114 | 69.4 | 54.4 | 2,062 | 67.7 | 64.9
California | 6,630 | 17.0 | 14.9 | 4,990 | 12.8 | 10.8 | 17,504 | 44.8 | 37.8 | 21,168 | 54.2 | 51.0
Colorado | 1,212 | 20.8 | 18.6 | 555 | 9.5 | 8.7 | 2,259 | 38.7 | 34.8 | 4,268 | 73.1 | 69.7
Connecticut | 535 | 14.8 | 12.0 | 763 | 21.0 | 15.2 | 2,022 | 55.8 | 40.8 | 2,640 | 72.8 | 66.5
Delaware | 170 | 16.7 | 12.3 | 205 | 20.1 | 14.4 | 619 | 60.8 | 43.7 | 883 | 86.7 | 83.8
District of Columbia | 61 | 9.1 | 9.0 | 49 | 7.3 | 7.2 | 226 | 33.6 | 33.1 | 635 | 94.5 | 90.9
Florida | 3,848 | 17.3 | 12.9 | 3,824 | 17.2 | 11.0 | 12,165 | 54.7 | 34.4 | 17,115 | 76.9 | 68.9
Georgia | 1,556 | 14.3 | 12.6 | 2,360 | 21.6 | 19.7 | 5,635 | 51.6 | 47.1 | 6,519 | 59.7 | 58.9
Hawaii | 145 | 10.1 | 7.8 | 300 | 20.8 | 13.5 | 444 | 30.8 | 20.3 | 693 | 48.1 | 40.9
Idaho | 315 | 16.2 | 14.2 | 176 | 9.1 | 7.6 | 823 | 42.4 | 36.3 | 1,163 | 60.0 | 57.9
Illinois | 1,807 | 14.4 | 12.1 | 2,916 | 23.2 | 18.2 | 7,281 | 57.9 | 45.5 | 7,597 | 60.4 | 55.9
Indiana | 1,212 | 17.7 | 15.3 | 1,541 | 22.6 | 18.6 | 4,577 | 67.0 | 54.9 | 4,989 | 73.0 | 71.6
Iowa | 522 | 16.3 | 14.3 | 488 | 15.2 | 11.1 | 1,714 | 53.6 | 39.7 | 1,845 | 57.6 | 49.8
Kansas | 481 | 16.4 | 14.6 | 644 | 21.9 | 17.4 | 2,043 | 69.6 | 56.1 | 1,995 | 67.9 | 63.8
Kentucky | 867 | 19.2 | 16.0 | 1,227 | 27.2 | 21.9 | 4,083 | 90.5 | 72.9 | 4,193 | 92.9 | 91.5
Louisiana | 649 | 14.1 | 11.8 | 1,072 | 23.4 | 19.3 | 2,360 | 51.4 | 43.1 | 4,320 | 94.1 | 93.9
Maine | 304 | 21.9 | 15.9 | 243 | 17.5 | 10.8 | 798 | 57.6 | 37.2 | 1,391 | 100.4 | 93.5
Maryland | 665 | 10.8 | 9.0 | 752 | 12.2 | 9.7 | 3,088 | 50.1 | 40.2 | 3,341 | 54.2 | 48.8
Massachusetts | 949 | 13.6 | 10.9 | 1,406 | 20.1 | 15.0 | 3,177 | 45.5 | 34.0 | 4,783 | 68.5 | 61.6
Michigan | 1,673 | 16.7 | 13.8 | 2,106 | 21.0 | 15.9 | 5,969 | 59.5 | 45.1 | 6,425 | 64.0 | 59.2
Minnesota | 908 | 15.9 | 13.5 | 607 | 10.6 | 8.2 | 2,299 | 40.2 | 31.3 | 3,882 | 67.9 | 61.1
Mississippi | 589 | 20.0 | 17.0 | 761 | 25.9 | 21.3 | 2,300 | 78.2 | 63.8 | 2,367 | 80.5 | 78.4
Missouri | 1,047 | 16.9 | 14.2 | 1,684 | 27.3 | 21.0 | 4,318 | 69.9 | 53.8 | 4,940 | 80.0 | 75.6
Montana | 274 | 24.4 | 21.4 | 164 | 14.6 | 11.0 | 516 | 46.0 | 33.6 | 803 | 71.5 | 65.4
Nebraska | 299 | 15.2 | 14.1 | 273 | 13.9 | 11.1 | 873 | 44.4 | 35.5 | 989 | 50.3 | 46.8
Nevada | 636 | 20.0 | 17.0 | 288 | 9.1 | 7.7 | 2,198 | 69.2 | 58.3 | 2,110 | 66.4 | 62.8
New Hampshire | 266 | 19.1 | 14.8 | 213 | 15.3 | 10.7 | 615 | 44.1 | 30.3 | 1,039 | 74.5 | 66.7
New Jersey | 989 | 10.7 | 8.6 | 1,768 | 19.1 | 14.6 | 4,947 | 53.4 | 40.6 | 4,956 | 53.5 | 49.7
New Mexico | 829 | 39.2 | 36.3 | 371 | 17.6 | 13.4 | 1,665 | 78.8 | 61.8 | 2,126 | 100.6 | 98.4
New York | 1,953 | 9.9 | 8.1 | 2,644 | 13.4 | 9.8 | 11,129 | 56.6 | 41.4 | 10,894 | 55.4 | 50.2
North Carolina | 1,801 | 16.8 | 13.8 | 2,169 | 20.3 | 16.4 | 6,275 | 58.7 | 47.4 | 8,858 | 82.8 | 80.0
North Dakota | 143 | 18.4 | 18.2 | 118 | 15.1 | 11.9 | 330 | 42.3 | 34.2 | 451 | 57.9 | 54.0
Ohio | 2,009 | 17.1 | 13.9 | 2,548 | 21.7 | 16.3 | 9,333 | 79.4 | 60.1 | 9,682 | 82.4 | 78.5
Oklahoma | 900 | 22.4 | 20.0 | 523 | 13.0 | 11.1 | 3,413 | 84.9 | 71.9 | 3,421 | 85.1 | 81.4
Oregon | 893 | 21.1 | 17.1 | 492 | 11.6 | 8.8 | 1,902 | 44.9 | 34.1 | 3,231 | 76.2 | 67.9
Pennsylvania | 1,834 | 14.1 | 10.8 | 3,135 | 24.2 | 16.7 | 8,745 | 67.4 | 47.5 | 10,060 | 77.6 | 70.4
Rhode Island | 205 | 18.7 | 14.9 | 124 | 11.3 | 8.0 | 535 | 48.9 | 35.0 | 848 | 77.5 | 67.6
South Carolina | 1,088 | 20.6 | 16.8 | 955 | 18.1 | 13.6 | 3,502 | 66.3 | 51.0 | 4,827 | 91.4 | 88.2
South Dakota | 283 | 31.1 | 31.1 | 81 | 8.9 | 7.2 | 453 | 49.8 | 39.4 | 600 | 65.9 | 60.7
Tennessee | 1,398 | 19.8 | 16.6 | 1,245 | 17.7 | 14.3 | 5,400 | 76.6 | 62.0 | 7,114 | 100.9 | 98.4
Texas | 5,079 | 16.9 | 15.9 | 4,766 | 15.9 | 16.0 | 14,573 | 48.5 | 49.0 | 15,252 | 50.8 | 51.1
Utah | 322 | 9.5 | 10.3 | 390 | 11.5 | 13.8 | 970 | 28.7 | 33.3 | 1,537 | 45.5 | 50.2
Vermont | 95 | 14.7 | 11.5 | 43 | 6.6 | 4.3 | 238 | 36.8 | 25.2 | 584 | 90.3 | 81.4
Virginia | 1,209 | 13.9 | 11.5 | 1,703 | 19.6 | 16.0 | 4,731 | 54.5 | 44.4 | 5,275 | 60.7 | 57.1
Washington | 1,371 | 17.6 | 15.1 | 577 | 7.4 | 6.2 | 2,918 | 37.5 | 31.6 | 5,546 | 71.2 | 66.2
West Virginia | 451 | 25.4 | 18.6 | 623 | 35.1 | 24.5 | 1,857 | 104.6 | 71.5 | 2,247 | 126.6 | 121.6
Wisconsin | 919 | 15.6 | 12.5 | 894 | 15.2 | 11.4 | 2,878 | 48.8 | 36.7 | 4,951 | 84.0 | 74.9
Wyoming | 162 | 27.9 | 24.3 | 82 | 14.1 | 11.1 | 291 | 50.1 | 40.0 | 411 | 70.7 | 65.3
Puerto Rico | 368 | 11.4 | 7.3 | 1,227 | 38.1 | 21.7 | 1,998 | 62.0 | 34.6 | 1,665 | 51.7 | 45.4
U.S. Virgin Islands | 3 | * | * | 16 | * | * | 29 | 27.5 | 19.2 | 32 | 30.4 | 27.3
Guam | 16 | * | * | 53 | 31.3 | 39.0 | 87 | 51.5 | 80.8 | 41 | 24.2 | 27.7
American Samoa | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 8 | * | * | 4 | * | * | 18 | * | * | 7 | * | *
Area | Motor vehicle accidents^3^ | | | Intentional self-harm (suicide) (*U03,X60–X84,Y87.0) | | | Assault (homicide) (*U01–^*^U02,X85–Y09,Y87.1) | | | Alcohol-induced causes^4^
Area | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^
United States^2^ | 46,027 | 13.8 | 13.3 | 49,476 | 14.8 | 14.2 | 24,849 | 7.5 | 7.7 | 51,191 | 15.4 | 13.5
Alabama | 1,039 | 20.5 | 20.0 | 840 | 16.6 | 16.3 | 706 | 13.9 | 14.9 | 502 | 9.9 | 8.9
Alaska | 117 | 15.9 | 15.6 | 200 | 27.3 | 27.6 | 76 | 10.4 | 10.2 | 286 | 39.0 | 36.6
Arizona | 1,366 | 18.6 | 17.8 | 1,603 | 21.8 | 20.6 | 629 | 8.5 | 9.0 | 1,623 | 22.1 | 20.2
Arkansas | 651 | 21.4 | 20.9 | 547 | 18.0 | 18.0 | 345 | 11.3 | 11.8 | 386 | 12.7 | 11.4
California | 5,041 | 12.9 | 12.4 | 4,312 | 11.0 | 10.4 | 2,304 | 5.9 | 5.9 | 6,708 | 17.2 | 15.5
Colorado | 836 | 14.3 | 13.7 | 1,293 | 22.1 | 21.1 | 417 | 7.1 | 7.2 | 1,581 | 27.1 | 24.5
Connecticut | 387 | 10.7 | 10.2 | 398 | 11.0 | 10.6 | 147 | 4.1 | 4.3 | 509 | 14.0 | 12.0
Delaware | 155 | 15.2 | 14.9 | 130 | 12.8 | 11.4 | 64 | 6.3 | 7.0 | 174 | 17.1 | 14.1
District of Columbia | 59 | 8.8 | 8.4 | 44 | 6.5 | 6.1 | 169 | 25.2 | 23.7 | 96 | 14.3 | 14.5
Florida | 3,706 | 16.7 | 15.9 | 3,446 | 15.5 | 14.1 | 1,473 | 6.6 | 7.2 | 3,262 | 14.7 | 11.7
Georgia | 1,908 | 17.5 | 17.1 | 1,624 | 14.9 | 14.6 | 1,223 | 11.2 | 11.3 | 1,273 | 11.7 | 10.6
Hawaii | 113 | 7.8 | 7.3 | 246 | 17.1 | 16.6 | 42 | 2.9 | 3.0 | 120 | 8.3 | 7.1
Idaho | 271 | 14.0 | 13.6 | 444 | 22.9 | 22.2 | 49 | 2.5 | 2.7 | 375 | 19.3 | 17.0
Illinois | 1,352 | 10.7 | 10.4 | 1,533 | 12.2 | 11.7 | 1,312 | 10.4 | 10.9 | 1,601 | 12.7 | 11.4
Indiana | 1,012 | 14.8 | 14.5 | 1,152 | 16.9 | 16.4 | 553 | 8.1 | 8.4 | 1,151 | 16.8 | 15.1
Iowa | 385 | 12.0 | 11.3 | 590 | 18.4 | 18.5 | 90 | 2.8 | 2.9 | 591 | 18.5 | 16.8
Kansas | 457 | 15.6 | 15.3 | 596 | 20.3 | 20.5 | 161 | 5.5 | 5.8 | 487 | 16.6 | 15.6
Kentucky | 786 | 17.4 | 16.7 | 823 | 18.2 | 18.0 | 348 | 7.7 | 8.3 | 646 | 14.3 | 12.6
Louisiana | 950 | 20.7 | 20.5 | 726 | 15.8 | 15.6 | 862 | 18.8 | 19.8 | 491 | 10.7 | 9.3
Maine | 201 | 14.5 | 13.7 | 268 | 19.3 | 17.7 | 32 | 2.3 | 2.6 | 317 | 22.9 | 18.5
Maryland | 626 | 10.2 | 9.8 | 608 | 9.9 | 9.5 | 658 | 10.7 | 11.4 | 601 | 9.7 | 8.6
Massachusetts | 479 | 6.9 | 6.3 | 626 | 9.0 | 8.3 | 171 | 2.4 | 2.5 | 959 | 13.7 | 11.8
Michigan | 1,223 | 12.2 | 11.7 | 1,503 | 15.0 | 14.7 | 801 | 8.0 | 8.6 | 1,598 | 15.9 | 13.9
Minnesota | 553 | 9.7 | 9.3 | 860 | 15.0 | 14.8 | 207 | 3.6 | 3.8 | 1,171 | 20.5 | 17.8
Mississippi | 763 | 26.0 | 25.8 | 417 | 14.2 | 14.0 | 576 | 19.6 | 20.7 | 442 | 15.0 | 13.0
Missouri | 1,111 | 18.0 | 17.3 | 1,219 | 19.7 | 19.1 | 744 | 12.0 | 12.8 | 911 | 14.7 | 13.3
Montana | 231 | 20.6 | 19.8 | 329 | 29.3 | 28.7 | 57 | 5.1 | 5.4 | 343 | 30.5 | 27.3
Nebraska | 279 | 14.2 | 14.2 | 306 | 15.5 | 15.6 | 73 | 3.7 | 3.7 | 371 | 18.9 | 18.1
Nevada | 440 | 13.8 | 13.4 | 698 | 22.0 | 21.0 | 244 | 7.7 | 7.8 | 759 | 23.9 | 20.7
New Hampshire | 154 | 11.0 | 9.8 | 247 | 17.7 | 16.6 | 25 | 1.8 | 1.8 | 295 | 21.1 | 17.1
New Jersey | 717 | 7.7 | 7.3 | 769 | 8.3 | 7.7 | 332 | 3.6 | 3.8 | 777 | 8.4 | 7.3
New Mexico | 486 | 23.0 | 23.4 | 525 | 24.8 | 24.7 | 290 | 13.7 | 14.5 | 925 | 43.8 | 42.7
New York | 1,384 | 7.0 | 6.6 | 1,765 | 9.0 | 8.5 | 853 | 4.3 | 4.5 | 2,003 | 10.2 | 8.8
North Carolina | 1,854 | 17.3 | 16.7 | 1,614 | 15.1 | 14.4 | 954 | 8.9 | 9.2 | 1,532 | 14.3 | 12.4
North Dakota | 108 | 13.9 | 13.5 | 169 | 21.7 | 22.5 | 28 | 3.6 | 3.5 | 195 | 25.0 | 25.0
Ohio | 1,395 | 11.9 | 11.5 | 1,798 | 15.3 | 15.0 | 929 | 7.9 | 8.5 | 1,707 | 14.5 | 12.4
Oklahoma | 777 | 19.3 | 18.9 | 857 | 21.3 | 21.4 | 317 | 7.9 | 8.3 | 836 | 20.8 | 19.3
Oregon | 616 | 14.5 | 13.7 | 883 | 20.8 | 19.3 | 212 | 5.0 | 5.1 | 1,264 | 29.8 | 24.5
Pennsylvania | 1,337 | 10.3 | 9.8 | 1,955 | 15.1 | 14.2 | 1,068 | 8.2 | 8.9 | 1,420 | 10.9 | 9.1
Rhode Island | 77 | 7.0 | 6.4 | 126 | 11.5 | 10.6 | 22 | 2.0 | 2.0 | 202 | 18.5 | 15.3
South Carolina | 1,141 | 21.6 | 21.4 | 853 | 16.1 | 15.4 | 595 | 11.3 | 11.8 | 954 | 18.1 | 15.3
South Dakota | 167 | 18.4 | 18.3 | 192 | 21.1 | 21.6 | 56 | 6.2 | 6.9 | 307 | 33.7 | 34.5
Tennessee | 1,338 | 19.0 | 18.5 | 1,245 | 17.7 | 16.7 | 738 | 10.5 | 11.0 | 1,328 | 18.8 | 16.4
Texas | 4,584 | 15.3 | 15.1 | 4,368 | 14.5 | 14.4 | 2,281 | 7.6 | 7.6 | 3,285 | 10.9 | 10.4
Utah | 323 | 9.6 | 9.7 | 718 | 21.2 | 22.1 | 72 | 2.1 | 2.2 | 373 | 11.0 | 11.8
Vermont | 81 | 12.5 | 11.5 | 128 | 19.8 | 18.0 | 18 | * | * | 144 | 22.3 | 16.8
Virginia | 1,086 | 12.5 | 11.8 | 1,208 | 13.9 | 13.3 | 653 | 7.5 | 7.8 | 965 | 11.1 | 9.6
Washington | 844 | 10.8 | 10.4 | 1,243 | 16.0 | 14.9 | 424 | 5.4 | 5.4 | 1,658 | 21.3 | 18.4
West Virginia | 290 | 16.3 | 15.1 | 353 | 19.9 | 18.3 | 105 | 5.9 | 6.2 | 304 | 17.1 | 13.7
Wisconsin | 661 | 11.2 | 10.5 | 924 | 15.7 | 15.1 | 327 | 5.5 | 6.0 | 1,177 | 20.0 | 16.6
Wyoming | 110 | 18.9 | 18.7 | 155 | 26.7 | 25.6 | 17 | * | * | 206 | 35.4 | 31.1
Puerto Rico | 282 | 8.8 | 8.3 | 201 | 6.2 | 5.7 | 585 | 18.2 | 19.9 | 274 | 8.5 | 5.9
U.S. Virgin Islands | 15 | * | * | 5 | * | * | 32 | 30.4 | 35.9 | 11 | * | *
Guam | 13 | * | * | 28 | 16.6 | 17.8 | 10 | * | * | 5 | * | *
American Samoa | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 5 | * | * | 6 | * | * | 3 | * | * | 2 | * | *
Area | Drug-induced causes^5^ | | | Injury by firearms^6^
Area | Number | Rate | Age-adjusted rate^1^ | Number | Rate | Age-adjusted rate^1^
United States^2^ | 112,109 | 33.6 | 33.8 | 48,204 | 14.5 | 14.2
Alabama | 1,632 | 32.2 | 34.3 | 1,278 | 25.2 | 25.5
Alaska | 273 | 37.2 | 36.7 | 164 | 22.4 | 22.4
Arizona | 2,799 | 38.0 | 39.0 | 1,535 | 20.9 | 20.1
Arkansas | 651 | 21.4 | 22.8 | 666 | 21.9 | 21.9
California | 11,393 | 29.2 | 28.0 | 3,484 | 8.9 | 8.6
Colorado | 1,882 | 32.2 | 30.9 | 1,036 | 17.7 | 17.1
Connecticut | 1,527 | 42.1 | 41.5 | 252 | 6.9 | 6.9
Delaware | 562 | 55.2 | 56.7 | 124 | 12.2 | 11.9
District of Columbia | 465 | 69.2 | 66.2 | 154 | 22.9 | 21.4
Florida | 7,776 | 35.0 | 36.1 | 3,232 | 14.5 | 14.0
Georgia | 2,804 | 25.7 | 26.0 | 2,163 | 19.8 | 19.7
Hawaii | 311 | 21.6 | 20.3 | 66 | 4.6 | 4.5
Idaho | 416 | 21.5 | 22.1 | 338 | 17.4 | 17.0
Illinois | 3,942 | 31.3 | 30.6 | 1,798 | 14.3 | 14.4
Indiana | 2,734 | 40.0 | 41.7 | 1,211 | 17.7 | 17.4
Iowa | 498 | 15.6 | 16.1 | 367 | 11.5 | 11.2
Kansas | 784 | 26.7 | 27.5 | 492 | 16.8 | 16.8
Kentucky | 2,375 | 52.6 | 55.4 | 840 | 18.6 | 18.8
Louisiana | 2,445 | 53.3 | 56.1 | 1,266 | 27.6 | 28.2
Maine | 726 | 52.4 | 55.6 | 179 | 12.9 | 11.7
Maryland | 2,636 | 42.8 | 41.2 | 813 | 13.2 | 13.6
Massachusetts | 2,787 | 39.9 | 39.3 | 263 | 3.8 | 3.7
Michigan | 3,065 | 30.5 | 31.3 | 1,504 | 15.0 | 15.0
Minnesota | 1,503 | 26.3 | 26.6 | 561 | 9.8 | 9.6
Mississippi | 791 | 26.9 | 28.7 | 848 | 28.8 | 29.6
Missouri | 2,264 | 36.6 | 38.0 | 1,489 | 24.1 | 24.2
Montana | 215 | 19.1 | 20.0 | 274 | 24.4 | 23.9
Nebraska | 249 | 12.7 | 13.0 | 244 | 12.4 | 12.2
Nevada | 1,046 | 32.9 | 31.6 | 618 | 19.4 | 18.9
New Hampshire | 496 | 35.5 | 36.6 | 156 | 11.2 | 10.1
New Jersey | 3,059 | 33.0 | 32.3 | 468 | 5.1 | 5.0
New Mexico | 1,056 | 50.0 | 51.9 | 571 | 27.0 | 27.3
New York | 6,564 | 33.4 | 32.4 | 1,044 | 5.3 | 5.3
North Carolina | 4,435 | 41.5 | 42.9 | 1,831 | 17.1 | 16.8
North Dakota | 157 | 20.1 | 21.0 | 125 | 16.0 | 16.4
Ohio | 5,312 | 45.2 | 47.0 | 1,831 | 15.6 | 15.6
Oklahoma | 1,244 | 30.9 | 31.9 | 797 | 19.8 | 19.8
Oregon | 1,563 | 36.9 | 35.1 | 655 | 15.4 | 14.4
Pennsylvania | 5,277 | 40.7 | 41.6 | 1,941 | 15.0 | 14.7
Rhode Island | 426 | 38.9 | 38.2 | 37 | 3.4 | 3.1
South Carolina | 2,373 | 44.9 | 46.4 | 1,105 | 20.9 | 20.8
South Dakota | 104 | 11.4 | 12.2 | 141 | 15.5 | 15.7
Tennessee | 3,955 | 56.1 | 57.9 | 1,480 | 21.0 | 20.5
Texas | 5,725 | 19.1 | 19.0 | 4,630 | 15.4 | 15.3
Utah | 668 | 19.8 | 21.1 | 446 | 13.2 | 13.7
Vermont | 284 | 43.9 | 47.2 | 84 | 13.0 | 12.0
Virginia | 2,615 | 30.1 | 30.1 | 1,316 | 15.2 | 14.9
Washington | 2,878 | 37.0 | 35.4 | 1,022 | 13.1 | 12.4
West Virginia | 1,405 | 79.1 | 84.8 | 311 | 17.5 | 16.2
Wisconsin | 1,834 | 31.1 | 32.4 | 830 | 14.1 | 14.0
Wyoming | 128 | 22.0 | 22.2 | 124 | 21.3 | 20.4
Puerto Rico | 831 | 25.8 | 27.3 | 597 | 18.5 | 20.2
U.S. Virgin Islands | 1 | * | * | 32 | 30.4 | 35.7
Guam | 2 | * | * | 7 | * | *
American Samoa | --- | --- | --- | --- | --- | ---
Northern Marianas | 1 | * | * | - | * | *

* Estimate does not meet National Center for Health Statistics standards of reliability or precision; see Technical Notes.

– Quantity zero

--- Data not available.

^1^Death rates are affected by the population composition of the area. Age-adjusted death rates should be used for comparisons between areas; for method of computation, see Technical Notes.

^2^Excludes data for Puerto Rico, U.S. Virgin Islands, Guam, American Samoa, and Northern Marianas.

^3^ICD–10 codes for Motor vehicle accidents are V02–V04, V09.0, V09.2, V12–V14, V19.0–V19.2, V19.4–V19.6, V20–V79, V80.3–V80.5, V81.0–V81.1, V82.0–V82.1, V83–V86, V87.0–V87.8, V88.0–V88.8, V89.0, and V89.2; see Technical Notes.

^4^Causes of death attributable to alcohol-induced mortality include ICD–10 codes E24.4, F10, G31.2, G62.1, G72.1, I42.6, K29.2, K70, K85.2, K86.0, R78.0, X45,X65, and Y15; see Technical Notes.

^5^Causes of death attributable to drug-induced mortality include ICD–10 codes D52.1 ,D59.0, D59.2, D61.1, D64.2, E06.4, E16.0, E23.1, E24.2, E27.3, E66.1, F11.1–F11.5, F11.7–F11.9, F12.1–F12.5, F12.7–F12.9, F13.1–F13.5, F13.7–F13.9, F14.1–F14.5, F14.7–F14.9, F15.1–F15.5, F15.7–F15.9, F16.1–F16.5, F16.7–F16.9, F17.3–F17.5, F17.7–F17.9, F18.1–F18.5, F18.7–F18.9, F19.1–F19.5, F19.7–F19.9, G21.1, G24.0, G25.1, G25.4, G25.6, G44.4, G62.0, G72.0, I95.2, J70.2–J70.4, K85.3, L10.5, L27.0–L27.1, M10.2, M32.0, M80.4, M81.4, M83.5, M87.1, R50.2, R78.1–R78.5, X40–X44, X60–X64, X85, and Y10–Y14; see Technical Notes.

^6^Causes of death attributable to Injury by firearms include ICD–10 codes *U01.4, W32–W34, X72–X74, X93–X95, Y22–Y24, and Y35.0; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 18 Infant, neonatal, and postneonatal mortality rates, by Hispanic origin and race and sex: United States, 1940, 1950, 1960, 1970, 1980, 1990, 2000–2022

[Rates are infant (younger then 1), neonatal (younger than 28 days), and postneonatal (28 days–11 months) deaths per 1,000 live births in specified group]

Hispanic origin and race and year | Infant mortality rate | | | Neonatal mortality rate | | | Postneonatal mortality rate
Hispanic origin and race and year | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All races and origins^1^
2022 | 5.60 | 6.07 | 5.12 | 3.58 | 3.80 | 3.34 | 2.03 | 2.26 | 1.78
2021 | 5.44 | 5.82 | 5.03 | 3.48 | 3.68 | 3.28 | 1.95 | 2.14 | 1.75
2020 | 5.42 | 5.88 | 4.94 | 3.56 | 3.84 | 3.26 | 1.86 | 2.04 | 1.68
2019 | 5.58 | 6.09 | 5.05 | 3.68 | 4.01 | 3.34 | 1.90 | 2.08 | 1.71
2018 | 5.66 | 6.23 | 5.07 | 3.77 | 4.13 | 3.39 | 1.89 | 2.09 | 1.68
2017 | 5.79 | 6.32 | 5.24 | 3.84 | 4.19 | 3.49 | 1.95 | 2.13 | 1.76
2016 | 5.87 | 6.38 | 5.34 | 3.87 | 4.19 | 3.54 | 2.00 | 2.19 | 1.80
2015 | 5.90 | 6.39 | 5.38 | 3.93 | 4.22 | 3.64 | 1.96 | 2.17 | 1.74
2014 | 5.82 | 6.31 | 5.30 | 3.94 | 4.25 | 3.62 | 1.88 | 2.07 | 1.68
2013 | 5.96 | 6.52 | 5.38 | 4.04 | 4.37 | 3.68 | 1.93 | 2.15 | 1.70
2012 | 5.98 | 6.50 | 5.43 | 4.01 | 4.34 | 3.67 | 1.97 | 2.16 | 1.76
2011 | 6.07 | 6.58 | 5.52 | 4.06 | 4.36 | 3.73 | 2.01 | 2.22 | 1.79
2010 | 6.15 | 6.69 | 5.57 | 4.05 | 4.37 | 3.71 | 2.10 | 2.32 | 1.87
2009 | 6.39 | 7.01 | 5.75 | 4.18 | 4.53 | 3.81 | 2.22 | 2.48 | 1.94
2008 | 6.61 | 7.21 | 5.97 | 4.29 | 4.67 | 3.89 | 2.32 | 2.54 | 2.08
2007 | 6.75 | 7.38 | 6.09 | 4.42 | 4.79 | 4.02 | 2.34 | 2.58 | 2.07
2006 | 6.69 | 7.32 | 6.03 | 4.45 | 4.84 | 4.05 | 2.24 | 2.48 | 1.98
2005 | 6.87 | 7.56 | 6.15 | 4.54 | 4.93 | 4.12 | 2.34 | 2.63 | 2.03
2004 | 6.79 | 7.47 | 6.09 | 4.52 | 4.94 | 4.09 | 2.27 | 2.53 | 2.00
2003 | 6.85 | 7.60 | 6.07 | 4.62 | 5.08 | 4.14 | 2.23 | 2.52 | 1.94
2002 | 6.97 | 7.64 | 6.27 | 4.66 | 5.06 | 4.25 | 2.31 | 2.58 | 2.03
2001 | 6.85 | 7.52 | 6.14 | 4.54 | 4.97 | 4.08 | 2.31 | 2.55 | 2.06
2000 | 6.91 | 7.57 | 6.21 | 4.63 | 5.06 | 4.17 | 2.28 | 2.51 | 2.04
1990 | 9.22 | 10.26 | 8.13 | 5.85 | 6.50 | 5.16 | 3.38 | 3.76 | 2.97
1980 | 12.60 | 13.93 | 11.21 | 8.48 | 9.31 | 7.60 | 4.13 | 4.62 | 3.61
1970 | 20.01 | 22.37 | 17.52 | 15.08 | 16.96 | 13.10 | 4.93 | 5.41 | 4.42
1960 | 26.04 | 29.33 | 22.59 | 18.73 | 21.24 | 16.09 | 7.31 | 8.10 | 6.49
1950 | 29.21 | 32.75 | 25.48 | 20.50 | 23.34 | 17.50 | 8.71 | 9.41 | 7.98
1940 | 47.02 | 52.45 | 41.29 | 28.75 | 32.56 | 24.74 | 18.27 | 19.89 | 16.55
Hispanic^23^
2022 | 5.08 | 5.47 | 4.68 | 3.47 | 3.65 | 3.28 | 1.62 | 1.82 | 1.40
2021 | 5.03 | 5.37 | 4.67 | 3.43 | 3.62 | 3.23 | 1.60 | 1.75 | 1.44
2020 | 4.89 | 5.36 | 4.40 | 3.38 | 3.70 | 3.05 | 1.51 | 1.66 | 1.35
2019 | 5.20 | 5.68 | 4.69 | 3.59 | 3.96 | 3.20 | 1.61 | 1.73 | 1.49
2018 | 5.06 | 5.55 | 4.56 | 3.54 | 3.88 | 3.18 | 1.52 | 1.67 | 1.38
2017 | 5.35 | 5.76 | 4.93 | 3.73 | 4.00 | 3.46 | 1.62 | 1.76 | 1.47
2016 | 5.24 | 5.72 | 4.75 | 3.63 | 3.94 | 3.30 | 1.62 | 1.78 | 1.45
2015 | 5.20 | 5.56 | 4.83 | 3.73 | 4.02 | 3.42 | 1.47 | 1.54 | 1.41
2014 | 5.22 | 5.63 | 4.79 | 3.67 | 3.98 | 3.34 | 1.55 | 1.66 | 1.45
2013 | 5.27 | 5.65 | 4.88 | 3.73 | 3.99 | 3.45 | 1.54 | 1.66 | 1.43
2012 | 5.30 | 5.76 | 4.83 | 3.71 | 4.05 | 3.35 | 1.60 | 1.71 | 1.47
2011 | 5.25 | 5.59 | 4.90 | 3.67 | 3.87 | 3.46 | 1.58 | 1.72 | 1.44
2010 | 5.47 | 5.96 | 4.96 | 3.73 | 4.07 | 3.37 | 1.74 | 1.89 | 1.59
2009 | 5.43 | 5.86 | 4.98 | 3.63 | 3.89 | 3.36 | 1.80 | 1.96 | 1.62
2008 | 5.66 | 6.16 | 5.13 | 3.81 | 4.16 | 3.45 | 1.84 | 2.00 | 1.68
2007 | 5.71 | 6.17 | 5.23 | 3.82 | 4.12 | 3.51 | 1.89 | 2.05 | 1.72
2006 | 5.52 | 5.99 | 5.03 | 3.79 | 4.07 | 3.49 | 1.73 | 1.92 | 1.53
2005 | 5.81 | 6.34 | 5.25 | 3.92 | 4.29 | 3.52 | 1.89 | 2.05 | 1.73
2004 | 5.62 | 6.10 | 5.12 | 3.84 | 4.17 | 3.49 | 1.78 | 1.93 | 1.63
2003 | 5.79 | 6.32 | 5.24 | 3.95 | 4.24 | 3.65 | 1.84 | 2.08 | 1.59
2002 | 5.64 | 6.14 | 5.11 | 3.80 | 4.13 | 3.45 | 1.84 | 2.01 | 1.66
2001 | 5.49 | 5.99 | 4.97 | 3.65 | 4.08 | 3.21 | 1.84 | 1.92 | 1.76
2000 | 5.64 | 6.04 | 5.22 | 3.74 | 4.01 | 3.45 | 1.90 | 2.02 | 1.77
Non-Hispanic, single race^24^
American Indian and Alaska Native:
2022 | 8.16 | 9.19 | 7.11 | 4.86 | 5.44 | 4.27 | 3.30 | 3.75 | 2.84
2021 | 7.46 | 7.87 | 7.04 | 3.71 | 3.67 | 3.76 | 3.75 | 4.20 | 3.29
2020 | 7.31 | 8.13 | 6.44 | 3.73 | 4.35 | 3.07 | 3.58 | 3.77 | 3.38
2019 | 8.05 | 8.55 | 7.53 | 4.11 | 4.00 | 4.23 | 3.94 | 4.55 | 3.30
2018 | 7.87 | 8.31 | 7.42 | 4.02 | 4.59 | 3.43 | 3.85 | 3.71 | 3.99
Asian:
2022 | 2.85 | 3.16 | 2.52 | 2.00 | 2.20 | 1.80 | 0.84 | 0.96 | 0.72
2021 | 2.94 | 3.20 | 2.66 | 2.26 | 2.36 | 2.15 | 0.68 | 0.84 | 0.51
2020 | 2.35 | 2.53 | 2.15 | 1.69 | 1.79 | 1.58 | 0.66 | 0.74 | 0.57
2019 | 2.63 | 2.89 | 2.35 | 1.91 | 2.10 | 1.71 | 0.72 | 0.79 | 0.63
2018 | 2.91 | 3.06 | 2.74 | 2.08 | 2.19 | 1.96 | 0.83 | 0.87 | 0.78
Black:
2022 | 11.34 | 12.42 | 10.22 | 6.58 | 7.20 | 5.93 | 4.76 | 5.23 | 4.29
2021 | 10.97 | 12.00 | 9.91 | 6.43 | 6.91 | 5.94 | 4.54 | 5.10 | 3.97
2020 | 10.85 | 11.75 | 9.92 | 6.74 | 7.28 | 6.18 | 4.11 | 4.47 | 3.75
2019 | 11.12 | 12.00 | 10.20 | 7.03 | 7.62 | 6.43 | 4.08 | 4.38 | 3.77
2018 | 11.10 | 12.35 | 9.81 | 7.13 | 7.93 | 6.31 | 3.97 | 4.42 | 3.50
Native Hawaiian or Other Pacific Islander:
2022 | 8.79 | 9.35 | 8.20 | 4.54 | 4.01 | 5.12 | 4.25 | 5.34 | *
2021 | 7.24 | 9.44 | 4.94 | 3.78 | 4.72 | * | 3.46 | 4.72 | *
2020 | 6.96 | 7.11 | 6.80 | 4.26 | 4.47 | * | 2.70 | * | *
2019 | 7.27 | 8.56 | 5.90 | 3.79 | 4.97 | * | 3.48 | * | *
2018 | 8.34 | 9.39 | 7.26 | 4.75 | 5.43 | * | 3.59 | * | *
White:
2022 | 4.39 | 4.74 | 4.02 | 2.85 | 3.00 | 2.70 | 1.53 | 1.74 | 1.31
2021 | 4.20 | 4.46 | 3.92 | 2.73 | 2.87 | 2.58 | 1.47 | 1.59 | 1.34
2020 | 4.29 | 4.62 | 3.94 | 2.84 | 3.04 | 2.63 | 1.45 | 1.58 | 1.31
2019 | 4.37 | 4.81 | 3.90 | 2.88 | 3.14 | 2.61 | 1.48 | 1.66 | 1.29
2018 | 4.55 | 4.98 | 4.09 | 3.02 | 3.27 | 2.76 | 1.53 | 1.71 | 1.34

* Estimate does not meet National Center for Health Statistics standards of reliability, see Technical Notes.

^1^Includes race and origin groups not shown separately; see Technical Notes.

^2^Infant deaths are based on race or Hispanic origin of child as stated on the death certificate; live births are based on race or Hispanic origin of mother as stated on the birth certificate; see Technical Notes.

^3^Includes persons of Hispanic origin of any race. The Hispanic-origin category is consistent with 1997 Office of Management and Budget (OMB) standards; see Technical Notes.

^4^Only one race was reported on the birth and death certificates; see Technical Notes. Hispanic origin and race categories are consistent with 1997 OMB standards.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 19 Number of infant deaths and infant mortality rate for 130 selected causes, by Hispanic origin and race: United States, 2022

[Rates are infant deaths (younger than 1) per 100,000 live births in specified group. Infant deaths are based on Hispanic origin and race of decedent; live births are based on Hispanic origin and race of mother. Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards. Asterisks (*) preceding cause-of-death codes indicate that they are not part of the International Classification of Diseases, 10th Revision (ICD–10); see Technical Notes. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10); see Technical Notes]

Cause of death (based on ICD–10) | Number | | | | | | | Rate
Cause of death (based on ICD–10) | Total^1^ | Hispanic^2^ | Non-Hispanic, single race^3^ | | | | | Total^1^ | Hispanic^2^ | Non-Hispanic, single race^3^
Cause of death (based on ICD–10) | Total^1^ | Hispanic^2^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian or Other Pacific Islander | White | Total^1^ | Hispanic^2^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian or Other Pacific Islander | White
All causes | 20,553 | 4,765 | 210 | 624 | 5,800 | 89 | 8,075 | 560.4 | 508.3 | 816.5 | 284.9 | 1,134.1 | 879.3 | 438.7
Certain infectious and parasitic diseases(A00–B99,U07.1)^4^ | 576 | 126 | 9 | 14 | 194 | 4 | 204 | 15.7 | 13.4 | * | * | 37.9 | * | 11.1
Certain intestinal infectious diseases(A00–A08) | 11 | – | – | 1 | 3 | – | 6 | * | * | * | * | * | * | *
Diarrhea and gastroenteritis of infectious origin(A09) | 135 | 32 | 2 | 1 | 51 | 2 | 39 | 3.7 | 3.4 | * | * | 10.0 | * | 2.1
Tuberculosis(A16–A19) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Tetanus(A33,A35) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Diphtheria(A36) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Whooping cough(A37) | 1 | – | – | – | – | – | 1 | * | * | * | * | * | * | *
Meningococcal infection(A39) | 1 | – | – | – | 1 | – | – | * | * | * | * | * | * | *
Septicemia(A40–A41) | 123 | 22 | 1 | 5 | 48 | 2 | 40 | 3.4 | 2.3 | * | * | 9.4 | * | 2.2
Congenital syphilis(A50) | 15 | 3 | 1 | – | 6 | – | 3 | * | * | * | * | * | * | *
Gonococcal infection(A54) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Viral diseases(A80–B34,U07.1)^4^ | 269 | 66 | 4 | 5 | 76 | – | 110 | 7.3 | 7.0 | * | * | 14.9 | * | 6.0
Acute poliomyelitis(A80) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Varicella (chickenpox)(B01) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Measles(B05) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Human immunodeficiency virus (HIV) disease(B20–B24) | 1 | – | 1 | – | – | – | – | * | * | * | * | * | * | *
Mumps(B26) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Other and unspecified viral diseases(A81–B00,B02–B04,B06–B19,B25,B27–B34,U07.1)^4^ | 268 | 66 | 3 | 5 | 76 | – | 110 | 7.3 | 7.0 | * | * | 14.9 | * | 6.0
Candidiasis(B37) | 2 | – | – | – | 2 | – | – | * | * | * | * | * | * | *
Malaria(B50–B54) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Pneumocystosis(B59) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
All other and unspecified infectious and parasitic diseases(A20–A32,A38,A42–A49,A51–A53,A55–A79,B35–B36,B38–B49,B55–B58,B60–B99) | 19 | 3 | 1 | 2 | 7 | – | 5 | * | * | * | * | * | * | *
Neoplasms(C00–D48) | 72 | 14 | – | 4 | 15 | 1 | 37 | 2.0 | * | * | * | * | * | 2.0
Malignant neoplasms(C00–C97) | 40 | 7 | – | 3 | 9 | 1 | 19 | 1.1 | * | * | * | * | * | *
Hodgkin disease and non-Hodgkin lymphomas(C81–C85) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Leukemia(C91–C95) | 14 | 4 | – | – | 3 | – | 7 | * | * | * | * | * | * | *
Other and unspecified malignant neoplasms(C00–C80,C88,C90,C96–C97) | 26 | 3 | – | 3 | 6 | 1 | 12 | 0.7 | * | * | * | * | * | *
In situ neoplasms, benign neoplasms and neoplasms of uncertain or unknown behavior(D00–D48) | 32 | 7 | – | 1 | 6 | – | 18 | 0.9 | * | * | * | * | * | *
Diseases of the blood and blood-forming organs and certain disorders involving the immune mechanism(D50–D89) | 94 | 25 | – | 4 | 29 | – | 32 | 2.6 | 2.7 | * | * | 5.7 | * | 1.7
Anemias(D50–D64) | 5 | 2 | – | – | 2 | – | 1 | * | * | * | * | * | * | *
Hemorrhagic conditions and other diseases of blood and blood-forming organs(D65–D76) | 68 | 20 | – | 2 | 22 | – | 22 | 1.9 | 2.1 | * | * | 4.3 | * | 1.2
Certain disorders involving the immune mechanism(D80–D89) | 21 | 3 | – | 2 | 5 | – | 9 | 0.6 | * | * | * | * | * | *
Endocrine, nutritional and metabolic diseases(E00–E88) | 151 | 40 | 1 | 7 | 31 | – | 67 | 4.1 | 4.3 | * | * | 6.1 | * | 3.6
Short stature, not elsewhere classified(E34.3) | 1 | – | – | – | – | – | 1 | * | * | * | * | * | * | *
Nutritional deficiencies(E40–E64) | 13 | 2 | – | – | 6 | – | 5 | * | * | * | * | * | * | *
Cystic fibrosis(E84) | 4 | – | – | – | 1 | – | 3 | * | * | * | * | * | * | *
Volume depletion, disorders of fluid, electrolyte and acid-base balance(E86–E87) | 31 | 11 | – | – | 11 | – | 8 | 0.8 | * | * | * | * | * | *
All other endocrine, nutritional and metabolic diseases(E00–E32,E34.0–E34.2,E34.4–E34.9,E65–E83,E85,E88) | 102 | 27 | 1 | 7 | 13 | – | 50 | 2.8 | 2.9 | * | * | * | * | 2.7
Diseases of the nervous system(G00–G98) | 226 | 50 | 1 | 15 | 57 | 1 | 92 | 6.2 | 5.3 | * | * | 11.1 | * | 5.0
Meningitis(G00,G03) | 43 | 9 | 1 | 4 | 15 | – | 11 | 1.2 | * | * | * | * | * | *
Infantile spinal muscular atrophy, type I (Werdnig-Hoffman)(G12.0) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Infantile cerebral palsy(G80) | 1 | – | – | – | 1 | – | – | * | * | * | * | * | * | *
Anoxic brain damage, not elsewhere classified(G93.1) | 31 | 4 | – | – | 7 | – | 18 | 0.8 | * | * | * | * | * | *
Other diseases of nervous system(G04,G06–G11,G12.1 –G12.9,G20–G72,G81–G92,G93.0,G93.2–G93.9,G95–G98) | 151 | 37 | – | 11 | 34 | 1 | 63 | 4.1 | 3.9 | * | * | 6.6 | * | 3.4
Diseases of the ear and mastoid process(H60–H93) | 1 | – | – | – | 1 | – | – | * | * | * | * | * | * | *
Diseases of the circulatory system(I00–I99) | 356 | 82 | 3 | 10 | 97 | 2 | 153 | 9.7 | 8.7 | * | * | 19.0 | * | 8.3
Pulmonary heart disease and diseases of pulmonary circulation(I26–I28) | 56 | 12 | – | 2 | 17 | – | 24 | 1.5 | * | * | * | * | * | 1.3
Pericarditis, endocarditis and myocarditis(I30,I33,I40) | 7 | 3 | – | – | 1 | – | 3 | * | * | * | * | * | * | *
Cardiomyopathy(I42) | 86 | 27 | 1 | 2 | 18 | 1 | 32 | 2.3 | 2.9 | * | * | * | * | 1.7
Cardiac arrest(I46) | 11 | 1 | – | – | 5 | – | 5 | * | * | * | * | * | * | *
Cerebrovascular diseases(I60–I69) | 87 | 21 | 2 | – | 26 | – | 36 | 2.4 | 2.2 | * | * | 5.1 | * | 2.0
All other diseases of circulatory system(I00–I25,I31,I34–I38,I44–I45,I47–I51,I70–I99) | 109 | 18 | – | 6 | 30 | 1 | 53 | 3.0 | * | * | * | 5.9 | * | 2.9
Diseases of the respiratory system(J00–J98,U04) | 387 | 70 | 8 | 12 | 121 | 2 | 154 | 10.6 | 7.5 | * | * | 23.7 | * | 8.4
Acute upper respiratory infections(J00–J06) | 9 | 1 | 1 | – | 3 | – | 3 | * | * | * | * | * | * | *
Influenza and pneumonia(J09–J18) | 154 | 29 | 4 | 5 | 47 | 2 | 55 | 4.2 | 3.1 | * | * | 9.2 | * | 3.0
Influenza(J09–J11) | 12 | 5 | 1 | 1 | – | – | 4 | * | * | * | * | * | * | *
Pneumonia(J12–J18) | 142 | 24 | 3 | 4 | 47 | 2 | 51 | 3.9 | 2.6 | * | * | 9.2 | * | 2.8
Acute bronchitis and acute bronchiolitis(J20–J21) | 40 | 12 | – | – | 14 | – | 14 | 1.1 | * | * | * | * | * | *
Bronchitis, chronic and unspecified(J40–J42) | 4 | 1 | 1 | – | 2 | – | – | * | * | * | * | * | * | *
Asthma(J45–J46) | 2 | – | – | 1 | – | – | 1 | * | * | * | * | * | * | *
Pneumonitis due to solids and liquids(J69) | 8 | 1 | – | – | 2 | – | 5 | * | * | * | * | * | * | *
Other and unspecified diseases of respiratory system(J22,J30–J39,J43–J44,J47–J68,J70–J98,U04) | 170 | 26 | 2 | 6 | 53 | – | 76 | 4.6 | 2.8 | * | * | 10.4 | * | 4.1
Diseases of the digestive system(K00–K92) | 140 | 39 | 2 | 3 | 31 | – | 58 | 3.8 | 4.2 | * | * | 6.1 | * | 3.2
Gastritis, duodenitis, and noninfective enteritis and colitis(K29,K50–K55) | 31 | 9 | 1 | 3 | 6 | – | 10 | 0.8 | * | * | * | * | * | *
Hernia of abdominal cavity and intestinal obstruction without hernia(K40–K46,K56) | 31 | 10 | 1 | – | 7 | – | 11 | 0.8 | * | * | * | * | * | *
All other and unspecified diseases of digestive system(K00–K28,K30–K38,K57–K92) | 78 | 20 | – | – | 18 | – | 37 | 2.1 | 2.1 | * | * | * | * | 2.0
Diseases of the genitourinary system(N00–N95) | 54 | 13 | 1 | 3 | 27 | – | 10 | 1.5 | * | * | * | 5.3 | * | *
Renal failure and other disorders of kidney(N17–N19,N25,N27) | 36 | 5 | 1 | 3 | 19 | – | 8 | 1.0 | * | * | * | * | * | *
Other and unspecified diseases of genitourinary system(N00–N15,N20–N23,N26,N28–N95) | 18 | 8 | – | – | 8 | – | 2 | * | * | * | * | * | * | *
Certain conditions originating in the perinatal period(P00–P96) | 10,068 | 2,386 | 80 | 362 | 2,928 | 40 | 3,764 | 274.5 | 254.5 | 311.0 | 165.3 | 572.5 | 395.2 | 204.5
Newborn affected by maternal factors and by complications of pregnancy, labor and delivery(P00–P04) | 2,224 | 531 | 23 | 98 | 611 | 12 | 805 | 60.6 | 56.6 | 89.4 | 44.8 | 119.5 | * | 43.7
Newborn affected by maternal hypertensive disorders(P00.0) | 65 | 11 | – | 4 | 18 | – | 29 | 1.8 | * | * | * | * | * | 1.6
Newborn affected by other maternal conditions which may be unrelated to present pregnancy(P00.1–P00.9) | 103 | 24 | 1 | 3 | 28 | 1 | 40 | 2.8 | 2.6 | * | * | 5.5 | * | 2.2
Newborn affected by maternal complications of pregnancy(P01) | 1,215 | 305 | 11 | 69 | 346 | 8 | 396 | 33.1 | 32.5 | * | 31.5 | 67.7 | * | 21.5
Newborn affected by incompetent cervix(P01.0) | 314 | 85 | 2 | 22 | 103 | 3 | 78 | 8.6 | 9.1 | * | 10.0 | 20.1 | * | 4.2
Newborn affected by premature rupture of membranes(P01.1) | 641 | 154 | 7 | 42 | 178 | 5 | 206 | 17.5 | 16.4 | * | 19.2 | 34.8 | * | 11.2
Newborn affected by multiple pregnancy(P01.5) | 69 | 18 | – | 2 | 12 | – | 35 | 1.9 | * | * | * | * | * | 1.9
Newborn affected by other maternal complications of pregnancy(P01.2–P01.4,P01.6–P01.9) | 191 | 48 | 2 | 3 | 53 | – | 77 | 5.2 | 5.1 | * | * | 10.4 | * | 4.2
Newborn affected by complications of placenta, cord and membranes(P02) | 649 | 139 | 8 | 17 | 170 | 2 | 268 | 17.7 | 14.8 | * | * | 33.2 | * | 14.6
Newborn affected by complications involving placenta(P02.0–P02.3) | 394 | 76 | 6 | 12 | 92 | – | 183 | 10.7 | 8.1 | * | * | 18.0 | * | 9.9
Newborn affected by complications involving cord(P02.4–P02.6) | 44 | 7 | – | – | 14 | – | 20 | 1.2 | * | * | * | * | * | 1.1
Newborn affected by chorioamnionitis(P02.7) | 210 | 56 | 2 | 5 | 64 | 2 | 64 | 5.7 | 6.0 | * | * | 12.5 | * | 3.5
Newborn affected by other and unspecified abnormalities of membranes(P02.8–P02.9) | 1 | – | – | – | – | – | 1 | * | * | * | * | * | * | *
Newborn affected by other complications of labor and delivery(P03) | 158 | 44 | 3 | 5 | 43 | – | 56 | 4.3 | 4.7 | * | * | 8.4 | * | 3.0
Newborn affected by noxious influences transmitted via placenta or breast milk(P04) | 34 | 8 | – | – | 6 | 1 | 16 | 0.9 | * | * | * | * | * | *
Disorders related to length of gestation and fetal malnutrition(P05–P08) | 2,967 | 696 | 17 | 104 | 992 | 11 | 987 | 80.9 | 74.2 | * | 47.5 | 194.0 | * | 53.6
Slow fetal growth and fetal malnutrition(P05) | 83 | 17 | 1 | 3 | 28 | 1 | 30 | 2.3 | * | * | * | 5.5 | * | 1.6
Disorders related to short gestation and low birth weight, not elsewhere classified(P07) | 2,884 | 679 | 16 | 101 | 964 | 10 | 957 | 78.6 | 72.4 | * | 46.1 | 188.5 | * | 52.0
Extremely low birth weight or extreme immaturity(P07.0,P07.2) | 2,213 | 536 | 13 | 80 | 743 | 8 | 706 | 60.3 | 57.2 | * | 36.5 | 145.3 | * | 38.4
Other low birth weight or preterm(P07.1,P07.3) | 671 | 143 | 3 | 21 | 221 | 2 | 251 | 18.3 | 15.3 | * | 9.6 | 43.2 | * | 13.6
Disorders related to long gestation and high birth weight(P08) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Birth trauma(P10–P15) | 20 | 2 | – | – | 4 | – | 13 | 0.5 | * | * | * | * | * | *
Intrauterine hypoxia and birth asphyxia(P20–P21) | 362 | 89 | 3 | 10 | 92 | 3 | 148 | 9.9 | 9.5 | * | * | 18.0 | * | 8.0
Intrauterine hypoxia(P20) | 213 | 57 | 1 | 6 | 60 | 2 | 77 | 5.8 | 6.1 | * | * | 11.7 | * | 4.2
Birth asphyxia(P21) | 149 | 32 | 2 | 4 | 32 | 1 | 71 | 4.1 | 3.4 | * | * | 6.3 | * | 3.9
Respiratory distress of newborn(P22) | 455 | 95 | 3 | 16 | 136 | – | 179 | 12.4 | 10.1 | * | * | 26.6 | * | 9.7
Other respiratory conditions originating in the perinatal period(P23–P28) | 844 | 174 | 10 | 15 | 255 | – | 358 | 23.0 | 18.6 | * | * | 49.9 | * | 19.4
Congenital pneumonia(P23) | 56 | 12 | – | 3 | 13 | – | 27 | 1.5 | * | * | * | * | * | 1.5
Neonatal aspiration syndromes(P24) | 46 | 9 | 1 | 3 | 8 | – | 24 | 1.3 | * | * | * | * | * | 1.3
Interstitial emphysema and related conditions originating in the perinatal period(P25) | 73 | 17 | 1 | 2 | 19 | – | 33 | 2.0 | * | * | * | * | * | 1.8
Pulmonary hemorrhage originating in the perinatal period(P26) | 136 | 28 | 3 | – | 49 | – | 52 | 3.7 | 3.0 | * | * | 9.6 | * | 2.8
Chronic respiratory disease originating in the perinatal period(P27) | 170 | 26 | – | 3 | 68 | – | 62 | 4.6 | 2.8 | * | * | 13.3 | * | 3.4
Atelectasis(P28.0–P28.1) | 283 | 61 | 4 | 3 | 84 | – | 121 | 7.7 | 6.5 | * | * | 16.4 | * | 6.6
All other respiratory conditions originating in the perinatal period(P28.2–P28.9) | 80 | 21 | 1 | 1 | 14 | – | 39 | 2.2 | 2.2 | * | * | * | * | 2.1
Infections specific to the perinatal period(P35–P39) | 808 | 196 | 3 | 36 | 225 | 8 | 306 | 22.0 | 20.9 | * | 16.4 | 44.0 | * | 16.6
Bacterial sepsis of newborn(P36) | 636 | 161 | 2 | 31 | 176 | 8 | 229 | 17.3 | 17.2 | * | 14.2 | 34.4 | * | 12.4
Omphalitis of newborn with or without mild hemorrhage(P38) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
All other infections specific to the perinatal period(P35,P37,P39) | 172 | 35 | 1 | 5 | 49 | – | 77 | 4.7 | 3.7 | * | * | 9.6 | * | 4.2
Hemorrhagic and hematological disorders of newborn(P50–P61) | 473 | 120 | 3 | 19 | 99 | – | 217 | 12.9 | 12.8 | * | * | 19.4 | * | 11.8
Neonatal hemorrhage(P50–P52,P54) | 334 | 92 | 1 | 10 | 67 | – | 153 | 9.1 | 9.8 | * | * | 13.1 | * | 8.3
Hemorrhagic disease of newborn(P53) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Hemolytic disease of newborn due to isoimmunization and other perinatal jaundice(P55–P59) | 11 | 1 | 1 | – | 3 | – | 4 | * | * | * | * | * | * | *
Hematological disorders(P60–P61) | 128 | 27 | 1 | 9 | 29 | – | 60 | 3.5 | 2.9 | * | * | 5.7 | * | 3.3
Syndrome of infant of a diabetic mother and neonatal diabetes mellitus(P70.0–P70.2) | 12 | 4 | – | 1 | 4 | – | 3 | * | * | * | * | * | * | *
Necrotizing enterocolitis of newborn(P77) | 355 | 91 | 5 | 10 | 112 | 2 | 119 | 9.7 | 9.7 | * | * | 21.9 | * | 6.5
Hydrops fetalis not due to hemolytic disease(P83.2) | 171 | 41 | 2 | 8 | 30 | 1 | 82 | 4.7 | 4.4 | * | * | 5.9 | * | 4.5
Other perinatal conditions(P29,P70.3–P70.9,P71–P76,P78–P81,P83.0–P83.1,P83.3–P83.9,P90–P96) | 1,377 | 347 | 11 | 45 | 368 | 3 | 547 | 37.5 | 37.0 | * | 20.5 | 72.0 | * | 29.7
Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 3,970 | 1,147 | 41 | 124 | 710 | 10 | 1,772 | 108.2 | 122.4 | 159.4 | 56.6 | 138.8 | * | 96.3
Anencephaly and similar malformations(Q00) | 275 | 85 | 5 | 6 | 27 | – | 137 | 7.5 | 9.1 | * | * | 5.3 | * | 7.4
Congenital hydrocephalus(Q03) | 68 | 25 | 1 | 1 | 13 | 1 | 25 | 1.9 | 2.7 | * | * | * | * | 1.4
Spina bifida(Q05) | 12 | 3 | – | – | 2 | – | 5 | * | * | * | * | * | * | *
Other congenital malformations of nervous system(Q01–Q02,Q04,Q06–Q07) | 270 | 85 | 4 | 5 | 42 | 2 | 117 | 7.4 | 9.1 | * | * | 8.2 | * | 6.4
Congenital malformations of heart(Q20–Q24) | 885 | 237 | 5 | 30 | 164 | 3 | 415 | 24.1 | 25.3 | * | 13.7 | 32.1 | * | 22.5
Other congenital malformations of circulatory system(Q25–Q28) | 187 | 52 | 2 | 8 | 33 | – | 84 | 5.1 | 5.5 | * | * | 6.5 | * | 4.6
Congenital malformations of respiratory system(Q30–Q34) | 175 | 49 | – | 5 | 42 | – | 75 | 4.8 | 5.2 | * | * | 8.2 | * | 4.1
Congenital malformations of digestive system(Q35–Q45) | 62 | 17 | – | 2 | 12 | – | 28 | 1.7 | * | * | * | * | * | 1.5
Congenital malformations of genitourinary system(Q50–Q64) | 370 | 109 | 4 | 11 | 62 | 2 | 170 | 10.1 | 11.6 | * | * | 12.1 | * | 9.2
Congenital malformations and deformations of musculoskeletal system, limbs and integument(Q65–Q85) | 427 | 118 | 4 | 19 | 87 | 2 | 178 | 11.6 | 12.6 | * | * | 17.0 | * | 9.7
Down syndrome(Q90) | 57 | 19 | – | 1 | 10 | – | 25 | 1.6 | * | * | * | * | * | 1.4
Edward syndrome(Q91.0–Q91.3) | 445 | 138 | 3 | 11 | 89 | – | 185 | 12.1 | 14.7 | * | * | 17.4 | * | 10.1
Patau syndrome(Q91.4–Q91.7) | 192 | 69 | 3 | 4 | 27 | – | 84 | 5.2 | 7.4 | * | * | 5.3 | * | 4.6
Other congenital malformations and deformations(Q10–Q18,Q86–Q89) | 433 | 113 | 8 | 20 | 76 | – | 194 | 11.8 | 12.1 | * | 9.1 | 14.9 | * | 10.5
Other chromosomal abnormalities, not elsewhere classified(Q92–Q99) | 112 | 28 | 2 | 1 | 24 | – | 50 | 3.1 | 3.0 | * | * | 4.7 | * | 2.7
Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified(R00–R99) | 2,691 | 499 | 42 | 38 | 972 | 20 | 981 | 73.4 | 53.2 | 163.3 | 17.4 | 190.1 | 197.6 | 53.3
Sudden infant death syndrome(R95) | 1,529 | 262 | 26 | 25 | 568 | 11 | 550 | 41.7 | 27.9 | 101.1 | 11.4 | 111.1 | * | 29.9
Other symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified(R00–R53,R55–R94,R96–R99) | 1,162 | 237 | 16 | 13 | 404 | 9 | 431 | 31.7 | 25.3 | * | * | 79.0 | * | 23.4
All other diseases(residual) | 18 | 4 | – | – | 6 | – | 6 | * | * | * | * | * | * | *
External causes of mortality(*U01,V01–Y84) | 1,749 | 270 | 22 | 28 | 581 | 9 | 745 | 47.7 | 28.8 | 85.5 | 12.8 | 113.6 | * | 40.5
Accidents (unintentional injuries)(V01–X59) | 1,354 | 197 | 17 | 24 | 457 | 6 | 580 | 36.9 | 21.0 | * | 11.0 | 89.4 | * | 31.5
Transport accidents(V01–V99) | 80 | 26 | 2 | 4 | 23 | – | 24 | 2.2 | 2.8 | * | * | 4.5 | * | 1.3
Motor vehicle accidents(V02–V04,V09.0,V09.2,V12–V14,V19.0–V19.2,V19.4–V19.6,V20–V79,V80.3–V80.5,V81.0–V81.1,V82.0–V82.1,V83–V86,V87.0–V87.8,V88.0–V88.8, V89.0,V89.2) | 79 | 25 | 2 | 4 | 23 | – | 24 | 2.2 | 2.7 | * | * | 4.5 | * | 1.3
Other and unspecified transport accidents(V01,V05–V06,V09.1,V09.3–V09.9,V10–V11,V15–V18,V19.3,V19.8–V19.9,V80.0–V80.2,V80.6–V80.9,V81.2–V81.9,V82.2–V82.9,V87.9,V88.9,V89.1,V89.3,V89.9,V90–V99) | 1 | 1 | – | – | – | – | – | * | * | * | * | * | * | *
Falls(W00–W19) | 6 | 2 | – | – | 1 | – | 2 | * | * | * | * | * | * | *
Accidental discharge of firearms(W32–W34) | – | – | – | – | – | – | – | * | * | * | * | * | * | *
Accidental drowning and submersion(W65–W74) | 39 | 8 | – | – | 7 | – | 21 | 1.1 | * | * | * | * | * | 1.1
Accidental suffocation and strangulation in bed(W75) | 1,040 | 137 | 12 | 17 | 375 | 6 | 435 | 28.4 | 14.6 | * | * | 73.3 | * | 23.6
Other accidental suffocation and strangulation(W76–W77,W81–W84) | 67 | 9 | – | – | 15 | – | 40 | 1.8 | * | * | * | * | * | 2.2
Accidental inhalation and ingestion of food or other objects causing obstruction of respiratory tract(W78–W80) | 39 | 6 | – | 1 | 13 | – | 15 | 1.1 | * | * | * | * | * | *
Accidents caused by exposure to smoke, fire and flames(X00–X09) | 15 | 2 | 1 | – | 2 | – | 10 | * | * | * | * | * | * | *
Accidental poisoning and exposure to noxious substances(X40–X49) | 28 | 2 | 1 | – | 8 | – | 16 | 0.8 | * | * | * | * | * | *
Other and unspecified accidents(W20–W31,W35–W64,W85–W99,X10–X39,X50–X59) | 40 | 5 | 1 | 2 | 13 | – | 17 | 1.1 | * | * | * | * | * | *
Assault (homicide)(*U01,X85–Y09) | 252 | 50 | 3 | 3 | 80 | 1 | 98 | 6.9 | 5.3 | * | * | 15.6 | * | 5.3
Assault (homicide) by hanging, strangulation and suffocation(X91) | 11 | 2 | – | – | 1 | – | 7 | * | * | * | * | * | * | *
Assault (homicide) by discharge of firearms(*U01.4,X93–X95) | 16 | 5 | – | 1 | 6 | – | 2 | * | * | * | * | * | * | *
Neglect, abandonment and other maltreatment syndromes(Y06–Y07) | 55 | 9 | – | 1 | 15 | – | 26 | 1.5 | * | * | * | * | * | 1.4
Assault (homicide) by other and unspecified means(*U01.0–^*^U01.3,^*^U01.5–^*^U01.9,X85–X90,X92,X96–X99,Y00–Y05,Y08–Y09) | 170 | 34 | 3 | 1 | 58 | 1 | 63 | 4.6 | 3.6 | * | * | 11.3 | * | 3.4
Complications of medical and surgical care(Y40–Y84) | 20 | 4 | – | 1 | 6 | 1 | 8 | 0.5 | * | * | * | * | * | *
Other external causes(Y10–Y36) | 123 | 19 | 2 | – | 38 | 1 | 59 | 3.4 | * | * | * | 7.4 | * | 3.2

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

– Quantity zero.

^1^Includes race and origin groups not shown separately; see Technical Notes.

^2^Includes people of Hispanic origin of any race; see Technical Notes.

^3^Only one race was reported on the death certificate.

^4^Beginning with data year 2020, COVID-19 (ICD–10 code U07.1) was newly added as a cause of death.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 20 Number of infant deaths and infant mortality rate, by Hispanic origin and race for the United States, each state, Puerto Rico, U.S. Virgin Islands, Guam, American Samoa, and Northern Marianas, and by sex for the United States: 2022

[Rates are infant (younger than 1) deaths per 1,000 live births in specified group. Infant deaths are based on Hispanic origin and race of decedent; live births are based on Hispanic origin and race of mother; see Technical Notes in this report. Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes]

Area and sex | Total^1^ | | Hispanic^2^ | | Non-Hispanic, single race^3^
Area and sex | Total^1^ | | Hispanic^2^ | | American Indian and Alaska Native | | Asian | | Black | | Native Hawaiian or Other Pacific Islander | | White
Area and sex | Number | Rate | Number | Rate | Number | Rate | Number | Rate | Number | Rate | Number | Rate | Number | Rate
United States^4^ | 20,553 | 5.60 | 4,765 | 5.08 | 210 | 8.16 | 624 | 2.85 | 5,800 | 11.34 | 89 | 8.79 | 8,075 | 4.39
Male | 11,371 | 6.07 | 2,612 | 5.47 | 120 | 9.19 | 356 | 3.16 | 3,230 | 12.42 | 49 | 9.35 | 4,469 | 4.74
Female | 9,182 | 5.12 | 2,153 | 4.68 | 90 | 7.11 | 268 | 2.52 | 2,570 | 10.22 | 40 | 8.20 | 3,606 | 4.02
Alabama | 386 | 6.64 | 28 | 4.49 | 2 | * | 1 | * | 201 | 12.51 | 1 | * | 144 | 4.27
Alaska | 62 | 6.62 | 5 | * | 19 | * | 3 | * | 2 | * | 2 | * | 24 | 5.17
Arizona | 486 | 6.19 | 219 | 6.29 | 30 | 8.73 | 13 | * | 45 | 10.17 | 2 | * | 141 | 4.62
Arkansas | 270 | 7.61 | 21 | 4.97 | – | * | 2 | * | 78 | 12.38 | 5 | * | 153 | 6.79
California | 1,697 | 4.05 | 907 | 4.46 | 10 | * | 136 | 2.39 | 191 | 9.53 | 17 | * | 330 | 2.99
Colorado | 286 | 4.58 | 108 | 5.69 | 2 | * | 10 | * | 29 | 9.73 | 1 | * | 106 | 3.02
Connecticut | 153 | 4.33 | 61 | 6.36 | – | * | 6 | * | 36 | 8.38 | – | * | 40 | 2.14
Delaware | 78 | 7.21 | 11 | * | – | * | 6 | * | 41 | 14.37 | – | * | 17 | *
District of Columbia | 39 | 4.83 | 3 | * | – | * | – | * | 28 | 8.01 | – | * | 4 | *
Florida | 1,341 | 5.98 | 373 | 4.98 | 2 | * | 13 | * | 512 | 10.75 | – | * | 402 | 4.38
Georgia | 894 | 7.09 | 115 | 5.42 | – | * | 24 | 4.26 | 469 | 11.16 | 2 | * | 272 | 5.07
Hawaii | 88 | 5.66 | 27 | 10.00 | – | * | 14 | * | – | * | 10 | * | 6 | *
Idaho | 117 | 5.23 | 21 | 5.25 | 3 | * | 1 | * | 3 | * | 1 | * | 84 | 4.97
Illinois | 715 | 5.57 | 146 | 4.91 | – | * | 22 | 2.66 | 242 | 12.54 | – | * | 273 | 4.01
Indiana | 574 | 7.21 | 78 | 7.85 | – | * | 10 | * | 150 | 14.82 | – | * | 313 | 5.67
Iowa | 193 | 5.29 | 24 | 5.75 | 2 | * | 3 | * | 32 | 12.49 | 3 | * | 120 | 4.36
Kansas | 207 | 6.02 | 50 | 7.93 | 1 | * | 6 | * | 21 | 9.51 | – | * | 117 | 4.94
Kentucky | 302 | 5.77 | 25 | 5.83 | – | * | 1 | * | 49 | 9.72 | 2 | * | 216 | 5.34
Louisiana | 414 | 7.33 | 29 | 4.89 | 2 | * | – | * | 242 | 11.96 | – | * | 134 | 4.77
Maine | 79 | 6.53 | 1 | * | – | * | – | * | 11 | * | – | * | 61 | 5.73
Maryland | 422 | 6.14 | 80 | 5.56 | – | * | 26 | 5.80 | 213 | 10.42 | – | * | 90 | 3.29
Massachusetts | 227 | 3.31 | 62 | 4.03 | – | * | 7 | * | 41 | 5.75 | – | * | 113 | 3.00
Michigan | 650 | 6.35 | 46 | 6.45 | 3 | * | 21 | 5.26 | 238 | 13.81 | – | * | 306 | 4.35
Minnesota | 289 | 4.51 | 24 | 3.97 | 6 | * | 15 | * | 82 | 10.35 | – | * | 142 | 3.36
Mississippi | 318 | 9.17 | 9 | * | 4 | * | 2 | * | 174 | 12.40 | – | * | 124 | 7.00
Missouri | 460 | 6.67 | 31 | 5.93 | – | * | 3 | * | 125 | 13.60 | 5 | * | 278 | 5.58
Montana | 53 | 4.74 | 4 | * | 7 | * | – | * | 1 | * | – | * | 37 | 4.11
Nebraska | 142 | 5.83 | 18 | * | 1 | * | 3 | * | 25 | 15.65 | 1 | * | 89 | 5.52
Nevada | 153 | 4.61 | 56 | 4.30 | 2 | * | 5 | * | 37 | 8.54 | 2 | * | 38 | 3.47
New Hampshire | 43 | 3.56 | 5 | * | – | * | – | * | 1 | * | – | * | 36 | 3.49
New Jersey | 371 | 3.61 | 112 | 3.74 | 1 | * | 23 | 2.18 | 117 | 9.06 | – | * | 109 | 2.30
New Mexico | 123 | 5.69 | 84 | 6.66 | 11 | * | 1 | * | 2 | * | – | * | 20 | 3.62
New York | 884 | 4.25 | 202 | 4.03 | 4 | * | 45 | 2.18 | 225 | 8.05 | – | * | 334 | 3.21
North Carolina | 826 | 6.79 | 120 | 5.32 | 12 | * | 16 | * | 339 | 12.85 | 1 | * | 300 | 4.78
North Dakota | 44 | 4.60 | 2 | * | 3 | * | 2 | * | 6 | * | – | * | 25 | 3.59
Ohio | 914 | 7.13 | 65 | 7.17 | – | * | 10 | * | 313 | 15.36 | 4 | * | 488 | 5.38
Oklahoma | 333 | 6.89 | 61 | 7.21 | 24 | 5.51 | 9 | * | 50 | 13.55 | 2 | * | 144 | 5.49
Oregon | 177 | 4.48 | 49 | 5.76 | 8 | * | 5 | * | 7 | * | 2 | * | 98 | 4.25
Pennsylvania | 742 | 5.70 | 109 | 6.02 | – | * | 25 | 4.02 | 189 | 11.37 | 3 | * | 369 | 4.34
Rhode Island | 39 | 3.80 | 19 | * | – | * | 3 | * | 3 | * | – | * | 9 | *
South Carolina | 390 | 6.75 | 30 | 4.24 | 1 | * | 3 | * | 191 | 12.46 | 1 | * | 149 | 4.61
South Dakota | 87 | 7.77 | 5 | * | 30 | 20.51 | – | * | 2 | * | – | * | 47 | 5.87
Tennessee | 541 | 6.58 | 48 | 4.34 | – | * | 2 | * | 166 | 11.44 | 1 | * | 299 | 5.66
Texas | 2,243 | 5.76 | 963 | 5.04 | 3 | * | 60 | 2.89 | 527 | 11.02 | 2 | * | 645 | 5.29
Utah | 224 | 4.89 | 52 | 5.83 | 1 | * | 2 | * | 11 | * | 5 | * | 143 | 4.41
Vermont | 25 | 4.70 | 3 | * | – | * | – | * | 1 | * | – | * | 19 | *
Virginia | 586 | 6.13 | 95 | 5.96 | 1 | * | 26 | 3.64 | 217 | 11.70 | - | * | 200 | 3.92
Washington | 360 | 4.32 | 99 | 5.76 | 9 | * | 24 | 2.62 | 34 | 8.95 | 13 | * | 141 | 3.20
West Virginia | 127 | 7.50 | 5 | * | – | * | – | * | 10 | * | – | * | 108 | 7.06
Wisconsin | 344 | 5.73 | 49 | 7.03 | 5 | * | 14 | * | 71 | 12.48 | 1 | * | 192 | 4.52
Wyoming | 35 | 5.79 | 6 | * | 1 | * | 1 | * | – | * | – | * | 26 | 5.63
Puerto Rico | 143 | 7.48 | 141 | 7.54 | – | * | – | * | – | * | – | * | 2 | *
U.S. Virgin Islands | 6 | * | 2 | * | – | * | – | * | 2 | * | – | * | 1 | *
Guam | 27 | 10.72 | 2 | * | – | * | 2 | * | – | * | 19 | * | – | *
American Samoa | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | ---
Northern Marianas | 6 | * | – | * | – | * | 1 | * | – | * | 5 | * | – | *

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

– Quantity zero.

--- Data not available.

^1^Includes race and origin groups not shown separately; see Technical Notes.

^2^Includes people of Hispanic origin of any race; see Technical Notes.

^3^Only one race was reported on the death certificate; see Technical Notes.

^4^Excludes data for Puerto Rico, U.S. Virgin Islands, Guam, American Samoa, and Northern Marianas.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 21 Number of maternal deaths and maternal mortality rate for selected causes, by Hispanic origin and race: United States, 2022

[Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards. Data for specified categories other than Black non-Hispanic, single race and White non-Hispanic, single race should be interpreted with caution because of inconsistencies between reporting these items on death certificates and on censuses and surveys; see Technical Notes in this report]

Cause of death (based on International Classification of Diseases, 10th Revision) | Total^1^ | Hispanic^2^ | Non-Hispanic, single race^3^
Cause of death (based on International Classification of Diseases, 10th Revision) | Total^1^ | Hispanic^2^ | American Indian and Alaska Native | Asian | Black | Native Hawaiian or Other Pacific Islander | White
| Number
Maternal causes(A34,O00–O95,O98–O99) | 817 | 158 | 12 | 29 | 253 | 4 | 350
Direct obstetric causes(A34, O00–O95) | 394 | 92 | 8 | 17 | 125 | 3 | 143
Pregnancy with abortive outcome(O00–O07) | 33 | 7 | 2 | 1 | 11 | 1 | 11
Ectopic pregnancy(O00) | 23 | 5 | 1 | – | 8 | 1 | 8
Spontaneous abortion(O03) | 5 | – | 1 | 1 | 1 | – | 2
Medical abortion(O04) | – | – | – | – | – | – | –
Other abortion(O05) | – | – | – | – | – | – | –
Other and unspecified pregnancy with abortive outcome(O01–O02,O06–O07) | 5 | 2 | – | – | 2 | – | 1
Other direct obstetric causes(A34,O10–O92) | 353 | 82 | 6 | 16 | 112 | 2 | 129
Eclampsia and pre–eclampsia(O11,O13–O16) | 37 | 10 | – | 2 | 11 | – | 13
Hemorrhage of pregnancy and childbirth and placenta previa(O20,O44–O46,O67,O72) | 34 | 7 | 1 | 3 | 10 | – | 12
Complications predominantly related to the puerperium(A34,O85–O92) | 77 | 18 | – | 3 | 29 | 2 | 24
Obstetrical tetanus(A34) | – | – | – | – | – | – | –
Obstetric embolism(O88) | 40 | 7 | – | 3 | 14 | 2 | 13
Other complications predominantly related to the puerperium(O85–O87,O89–O92) | 37 | 11 | – | – | 15 | – | 11
All other direct obstetric causes(O10,O12,O21–O43,O47–O66,O68–O71,O73–O75) | 205 | 47 | 5 | 8 | 62 | – | 80
Obstetric death of unspecified cause(O95) | 8 | 3 | – | – | 2 | – | 3
Indirect obstetric causes(O98–O99) | 423 | 66 | 4 | 12 | 128 | 1 | 207
Death from any obstetric cause occurring more than 42 days but less than 1 year after delivery (O96)^4^ | 428 | 68 | 14 | 17 | 129 | 1 | 197
| Rate per 100,000 live births
Maternal causes(A34,O00–O95,O98–O99) | 22.3 | 16.9 | * | 13.2 | 49.5 | * | 19.0
Direct obstetric causes(A34, O00–O95) | 10.7 | 9.8 | * | * | 24.4 | * | 7.8
Pregnancy with abortive outcome(O00–O07) | 0.9 | * | * | * | * | * | *
Ectopic pregnancy(O00) | 0.6 | * | * | * | * | * | *
Spontaneous abortion(O03) | * | * | * | * | * | * | *
Medical abortion(O04) | * | * | * | * | * | * | *
Other abortion(O05) | * | * | * | * | * | * | *
Other and unspecified pregnancy with abortive outcome(O01–O02,O06–O07) | * | * | * | * | * | * | *
Other direct obstetric causes(A34,O10–O92) | 9.6 | 8.7 | * | * | 21.9 | * | 7.0
Eclampsia and pre–eclampsia(O11,O13–O16) | 1.0 | * | * | * | * | * | *
Hemorrhage of pregnancy and childbirth and placenta previa(O20,O44–O46,O67,O72) | 0.9 | * | * | * | * | * | *
Complications predominantly related to the puerperium(A34,O85–O92) | 2.1 | * | * | * | 5.7 | * | 1.3
Obstetrical tetanus(A34) | * | * | * | * | * | * | *
Obstetric embolism(O88) | 1.1 | * | * | * | * | * | *
Other complications predominantly related to the puerperium(O85–O87,O89–O92) | 1.0 | * | * | * | * | * | *
All other direct obstetric causes(O10,O12,O21–O43,O47–O66,O68–O71,O73–O75) | 5.6 | 5.0 | * | * | 12.1 | * | 4.3
Obstetric death of unspecified cause(O95) | * | * | * | * | * | * | *
Indirect obstetric causes(O98–O99) | 11.5 | 7.0 | * | * | 25.0 | * | 11.2
Death from any obstetric cause occurring more than 42 days but less than 1 year after delivery (O96)^4^ | 11.7 | 7.3 | * | * | 25.2 | * | 10.7

– Quantity zero.

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

^1^Includes deaths with origin not stated, origin not classifiable, and two or more races reported; see Technical Notes.

^2^Includes people of Hispanic origin of any race; see Technical Notes.

^3^Only one race was reported on the death certificate; see Technical Notes.

^4^Late maternal death.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 22 Number of deaths, death rate, and age-adjusted death rate for dementia-related causes, by Hispanic origin and race and sex: United States, 1999–2022

[Excludes deaths of nonresidents of the United States]

Hispanic origin and race and year | Number | | | Crude death rate^1^ | | | Age-adjusted death rate^2^
Hispanic origin and race and year | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All origins and races^3^
2022 | 292,881 | 97,470 | 195,411 | 87.9 | 59.0 | 116.3 | 70.4 | 59.7 | 76.8
2021 | 279,704 | 92,303 | 187,401 | 84.3 | 56.2 | 111.9 | 72.4 | 59.7 | 80.2
2020 | 303,984 | 99,157 | 204,827 | 92.3 | 61.1 | 122.5 | 73.3 | 60.5 | 81.1
2019 | 271,872 | 90,482 | 181,390 | 82.8 | 56.0 | 108.9 | 66.6 | 56.6 | 72.6
2018 | 266,957 | 87,759 | 179,198 | 81.6 | 54.5 | 107.9 | 66.6 | 56.4 | 72.5
2017 | 261,914 | 85,129 | 176,785 | 80.4 | 53.1 | 106.9 | 66.7 | 56.4 | 72.7
2016 | 249,605 | 80,680 | 168,925 | 77.2 | 50.7 | 103.0 | 64.9 | 55.1 | 70.5
2015 | 245,926 | 79,113 | 166,813 | 76.5 | 50.0 | 102.2 | 65.2 | 55.4 | 70.7
2014 | 239,753 | 76,911 | 162,842 | 75.2 | 49.0 | 100.6 | 64.9 | 55.5 | 70.2
2013 | 234,242 | 74,656 | 159,586 | 74.1 | 48.0 | 99.4 | 64.8 | 55.4 | 69.8
2012 | 223,404 | 71,158 | 152,246 | 71.2 | 46.1 | 95.5 | 63.3 | 54.7 | 68.0
2011 | 212,876 | 67,053 | 145,823 | 68.3 | 43.7 | 92.1 | 61.8 | 53.1 | 66.3
2010 | 196,371 | 61,961 | 134,410 | 63.6 | 40.8 | 85.6 | 58.8 | 51.1 | 62.8
2009 | 177,523 | 55,553 | 121,970 | 57.9 | 36.8 | 78.2 | 54.2 | 46.8 | 57.9
2008 | 178,960 | 54,893 | 124,067 | 58.9 | 36.7 | 80.2 | 55.9 | 47.5 | 60.1
2007 | 156,042 | 47,537 | 108,505 | 51.8 | 32.1 | 70.8 | 49.8 | 42.4 | 53.5
2006 | 151,432 | 45,937 | 105,495 | 50.8 | 31.3 | 69.5 | 49.5 | 42.2 | 52.9
2005 | 129,573 | 38,024 | 91,549 | 43.8 | 26.2 | 60.9 | 43.4 | 36.1 | 46.9
2004 | 114,271 | 33,467 | 80,804 | 39.0 | 23.3 | 54.2 | 39.1 | 32.7 | 42.3
2003 | 110,569 | 32,246 | 78,323 | 38.1 | 22.6 | 53.0 | 38.4 | 32.1 | 41.4
2002 | 102,105 | 29,891 | 72,214 | 35.5 | 21.2 | 49.3 | 36.1 | 30.6 | 38.6
2001 | 92,514 | 27,315 | 65,199 | 32.5 | 19.5 | 44.9 | 33.1 | 28.5 | 35.2
2000 | 83,694 | 24,568 | 59,126 | 29.7 | 17.8 | 41.2 | 30.5 | 26.1 | 32.4
1999 | 74,386 | 22,380 | 52,006 | 26.7 | 16.4 | 36.6 | 27.5 | 24.2 | 28.9
Hispanic^4^
2022 | 19,213 | 6,209 | 13,004 | 30.2 | 19.2 | 41.4 | 54.3 | 45.7 | 59.2
2021 | 17,876 | 5,815 | 12,061 | 28.5 | 18.3 | 39.0 | 53.8 | 44.2 | 59.6
2020 | 18,534 | 6,151 | 12,383 | 30.2 | 19.9 | 40.7 | 54.3 | 46.1 | 59.3
2019 | 15,412 | 5,243 | 10,169 | 25.4 | 17.2 | 33.9 | 47.3 | 41.2 | 50.9
2018 | 14,937 | 5,181 | 9,756 | 24.9 | 17.1 | 32.9 | 47.4 | 42.1 | 50.3
2017 | 13,820 | 4,634 | 9,186 | 23.4 | 15.6 | 31.5 | 46.0 | 39.7 | 49.8
2016 | 12,687 | 4,278 | 8,409 | 22.1 | 14.7 | 29.6 | 44.8 | 38.9 | 48.3
2015 | 12,104 | 4,111 | 7,993 | 21.4 | 14.4 | 28.6 | 45.2 | 39.5 | 48.5
2014 | 11,583 | 3,987 | 7,596 | 20.9 | 14.2 | 27.8 | 46.3 | 41.2 | 49.3
2013 | 10,767 | 3,588 | 7,179 | 19.9 | 13.1 | 27.0 | 46.2 | 39.8 | 49.7
2012 | 9,943 | 3,411 | 6,532 | 18.8 | 12.7 | 25.0 | 45.7 | 40.6 | 48.4
2011 | 8,793 | 2,995 | 5,798 | 16.9 | 11.3 | 22.6 | 43.1 | 38.2 | 45.9
2010 | 7,744 | 2,717 | 5,027 | 15.3 | 10.6 | 20.2 | 41.7 | 38.2 | 43.5
2009 | 6,535 | 2,203 | 4,332 | 13.2 | 8.8 | 17.9 | 36.7 | 32.2 | 39.2
2008 | 6,378 | 2,127 | 4,251 | 13.3 | 8.7 | 18.1 | 38.2 | 32.8 | 40.9
2007 | 5,198 | 1,774 | 3,424 | 11.3 | 7.5 | 15.1 | 33.0 | 29.7 | 34.7
2006 | 5,076 | 1,757 | 3,319 | 11.4 | 7.7 | 15.2 | 33.9 | 30.6 | 35.4
2005 | 3,876 | 1,356 | 2,520 | 9.0 | 6.2 | 12.0 | 27.6 | 25.5 | 28.5
2004 | 3,244 | 1,059 | 2,185 | 7.8 | 5.0 | 10.8 | 24.5 | 21.2 | 26.2
2003 | 3,001 | 1,032 | 1,969 | 7.5 | 5.0 | 10.1 | 23.8 | 21.8 | 24.7
2002 | 2,461 | 840 | 1,621 | 6.4 | 4.2 | 8.6 | 20.7 | 19.0 | 21.5
2001 | 2,184 | 736 | 1,448 | 5.9 | 3.9 | 8.0 | 19.1 | 17.0 | 20.1
2000 | 1,867 | 671 | 1,196 | 5.3 | 3.7 | 7.0 | 17.2 | 16.0 | 17.6
1999 | 1,677 | 563 | 1,114 | 4.9 | 3.2 | 6.8 | 16.4 | 14.8 | 17.2
Non-Hispanic, single race^5^
American Indian and Alaska Native:
2022 | 897 | 300 | 597 | 37.1 | 25.1 | 48.8 | 39.8 | 31.5 | 45.5
2021 | 874 | 264 | 610 | 35.6 | 21.8 | 49.1 | 43.0 | 30.0 | 51.6
2020 | 864 | 278 | 586 | 35.5 | 23.3 | 47.4 | 43.0 | 32.6 | 49.9
2019 | 733 | 254 | 479 | 30.1 | 21.2 | 38.7 | 39.2 | 32.3 | 43.3
2018 | 764 | 270 | 494 | 31.6 | 22.7 | 40.2 | 42.7 | 36.2 | 46.5
Asian:
2022 | 7,591 | 2,463 | 5,128 | 37.4 | 25.2 | 48.8 | 36.1 | 30.0 | 39.8
2021 | 6,793 | 2,189 | 4,604 | 34.5 | 23.2 | 45.0 | 35.9 | 29.1 | 40.2
2020 | 7,120 | 2,288 | 4,832 | 36.8 | 24.7 | 47.8 | 36.8 | 30.0 | 41.1
2019 | 5,931 | 1,932 | 3,999 | 31.4 | 21.4 | 40.4 | 32.6 | 27.0 | 35.9
2018 | 5,529 | 1,799 | 3,730 | 29.5 | 20.2 | 38.0 | 32.3 | 26.8 | 35.6
Black:
2022 | 23,599 | 7,687 | 15,912 | 56.1 | 38.0 | 72.8 | 67.8 | 62.5 | 69.9
2021 | 23,685 | 7,506 | 16,179 | 56.6 | 37.3 | 74.4 | 71.8 | 62.7 | 75.9
2020 | 25,815 | 8,213 | 17,602 | 62.3 | 41.5 | 81.4 | 74.7 | 66.4 | 78.2
2019 | 21,629 | 7,067 | 14,562 | 52.6 | 35.9 | 67.8 | 64.5 | 59.6 | 66.3
2018 | 21,037 | 6,743 | 14,294 | 51.4 | 34.5 | 67.0 | 64.8 | 59.1 | 67.0
Native Hawaiian or Other Pacific Islander:
2022 | 202 | 70 | 132 | 31.8 | 21.8 | 42.0 | 42.5 | 31.9 | 50.2
2021 | 170 | 61 | 109 | 27.1 | 19.3 | 35.2 | 39.9 | 32.0 | 45.3
2020 | 171 | 71 | 100 | 27.9 | 23.0 | 32.9 | 40.3 | 37.4 | 42.1
2019 | 147 | 64 | 83 | 24.7 | 21.3 | 28.0 | 38.1 | 36.9 | 38.7
2018 | 126 | 50 | 76 | 21.5 | 16.9 | 26.1 | 35.5 | 31.2 | 38.3
White:
2022 | 240,132 | 80,270 | 159,862 | 122.4 | 82.3 | 162.0 | 75.2 | 63.4 | 82.6
2021 | 229,199 | 76,082 | 153,117 | 116.4 | 77.9 | 154.5 | 77.4 | 63.5 | 86.3
2020 | 250,280 | 81,744 | 168,536 | 127.2 | 84.2 | 169.0 | 77.8 | 63.7 | 86.8
2019 | 226,969 | 75,549 | 151,420 | 115.0 | 77.6 | 151.4 | 71.2 | 59.9 | 78.1
2018 | 223,473 | 73,273 | 150,200 | 113.1 | 75.2 | 150.0 | 70.9 | 59.4 | 77.8

^1^Rates are on an annual basis per 100,000 population in specified group; see Technical Notes in this report.

^2^Age-adjusted rates are per 100,000 U.S. standard population. For method of computation, see Technical Notes.

^3^Includes origins and races not shown separately; see Technical Notes.

^4^Includes people of Hispanic origin of any race. The Hispanic-origin category is consistent with 1997 Office of Management and Budget (OMB) standards; see Technical Notes.

^5^Only one race was reported on the death certificate. Hispanic-origin and race categories are consistent with 1997 OMB standards; see Technical Notes.

NOTE: Causes of death attributable to dementia-related mortality include International Classification of Diseases, 10th Revision codes F01 (Vascular dementia), F03 (Unspecified dementia), G30 (Alzheimer disease), and G31 (Other degenerative diseases of nervous system, not elsewhere classified).

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 23 Number of deaths, death rate, and age-adjusted death rate for drug-induced causes, by Hispanic origin and race and sex: United States, 1999–2022

[Excludes deaths of nonresidents of the United States]

Hispanic origin and race and year | Number | | | Crude death rate^1^ | | | Age-adjusted death rate^2^
Hispanic origin and race and year | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All origins and races^3^
2022 | 112,109 | 78,614 | 33,495 | 33.6 | 47.6 | 19.9 | 33.8 | 47.2 | 20.2
2021 | 111,219 | 77,309 | 33,910 | 33.5 | 47.0 | 20.2 | 33.6 | 46.8 | 20.4
2020 | 96,096 | 66,607 | 29,489 | 29.2 | 41.1 | 17.6 | 29.5 | 41.1 | 17.9
2019 | 74,511 | 50,393 | 24,118 | 22.7 | 31.2 | 14.5 | 22.8 | 31.1 | 14.5
2018 | 71,147 | 47,338 | 23,809 | 21.7 | 29.4 | 14.3 | 21.8 | 29.3 | 14.3
2017 | 73,990 | 48,967 | 25,023 | 22.7 | 30.5 | 15.1 | 22.8 | 30.5 | 15.2
2016 | 67,265 | 43,931 | 23,334 | 20.8 | 27.6 | 14.2 | 20.8 | 27.6 | 14.2
2015 | 55,403 | 34,815 | 20,588 | 17.2 | 22.0 | 12.6 | 17.2 | 21.9 | 12.5
2014 | 49,714 | 30,510 | 19,204 | 15.6 | 19.4 | 11.9 | 15.5 | 19.3 | 11.7
2013 | 46,471 | 28,381 | 18,090 | 14.7 | 18.2 | 11.3 | 14.6 | 18.0 | 11.1
2012 | 43,819 | 26,594 | 17,225 | 14.0 | 17.2 | 10.8 | 13.8 | 17.0 | 10.7
2011 | 43,544 | 26,444 | 17,100 | 14.0 | 17.3 | 10.8 | 13.9 | 17.0 | 10.7
2010 | 40,393 | 24,376 | 16,017 | 13.1 | 16.1 | 10.2 | 12.9 | 15.9 | 10.0
2009 | 39,147 | 24,015 | 15,132 | 12.8 | 15.9 | 9.7 | 12.6 | 15.7 | 9.5
2008 | 38,649 | 23,928 | 14,721 | 12.7 | 16.0 | 9.5 | 12.6 | 15.8 | 9.4
2007 | 38,371 | 23,883 | 14,488 | 12.7 | 16.1 | 9.5 | 12.6 | 16.0 | 9.3
2006 | 38,396 | 24,507 | 13,889 | 12.9 | 16.7 | 9.2 | 12.8 | 16.6 | 9.1
2005 | 33,541 | 21,208 | 12,333 | 11.3 | 14.6 | 8.2 | 11.3 | 14.5 | 8.1
2004 | 30,711 | 19,362 | 11,349 | 10.5 | 13.5 | 7.6 | 10.5 | 13.4 | 7.6
2003 | 28,723 | 18,426 | 10,297 | 9.9 | 12.9 | 7.0 | 9.9 | 12.9 | 7.0
2002 | 26,040 | 16,734 | 9,306 | 9.1 | 11.8 | 6.4 | 9.1 | 11.8 | 6.3
2001 | 21,705 | 14,253 | 7,452 | 7.6 | 10.2 | 5.1 | 7.6 | 10.1 | 5.1
2000 | 19,720 | 13,137 | 6,583 | 7.0 | 9.5 | 4.6 | 7.0 | 9.5 | 4.6
1999 | 19,128 | 12,885 | 6,243 | 6.9 | 9.4 | 4.4 | 6.8 | 9.4 | 4.4
Hispanic^4^
2022 | 14,573 | 11,563 | 3,010 | 22.9 | 35.8 | 9.6 | 23.4 | 36.3 | 9.9
2021 | 13,436 | 10,513 | 2,923 | 21.4 | 33.1 | 9.5 | 21.9 | 33.5 | 9.7
2020 | 11,059 | 8,725 | 2,334 | 18.0 | 28.2 | 7.7 | 18.4 | 28.5 | 7.9
2019 | 7,837 | 6,106 | 1,731 | 12.9 | 20.0 | 5.8 | 13.4 | 20.5 | 6.0
2018 | 6,663 | 5,087 | 1,576 | 11.1 | 16.8 | 5.3 | 11.6 | 17.5 | 5.6
2017 | 6,322 | 4,797 | 1,525 | 10.7 | 16.1 | 5.2 | 11.2 | 16.8 | 5.5
2016 | 5,540 | 4,130 | 1,410 | 9.6 | 14.2 | 5.0 | 10.1 | 14.8 | 5.3
2015 | 4,387 | 3,175 | 1,212 | 7.8 | 11.1 | 4.3 | 8.2 | 11.7 | 4.7
2014 | 3,790 | 2,687 | 1,103 | 6.8 | 9.6 | 4.0 | 7.3 | 10.3 | 4.4
2013 | 3,616 | 2,546 | 1,070 | 6.7 | 9.3 | 4.0 | 7.3 | 10.0 | 4.4
2012 | 3,272 | 2,283 | 989 | 6.2 | 8.5 | 3.8 | 6.8 | 9.3 | 4.2
2011 | 3,152 | 2,175 | 977 | 6.1 | 8.2 | 3.8 | 6.6 | 8.9 | 4.3
2010 | 2,788 | 1,944 | 844 | 5.5 | 7.6 | 3.4 | 6.1 | 8.4 | 3.8
2009 | 2,811 | 2,013 | 798 | 5.7 | 8.0 | 3.3 | 6.4 | 8.9 | 3.7
2008 | 2,761 | 2,033 | 728 | 5.8 | 8.4 | 3.1 | 6.4 | 9.3 | 3.5
2007 | 2,723 | 2,045 | 678 | 5.9 | 8.7 | 3.0 | 6.6 | 9.7 | 3.4
2006 | 2,871 | 2,135 | 736 | 6.4 | 9.4 | 3.4 | 7.3 | 10.6 | 3.9
2005 | 2,596 | 1,969 | 627 | 6.0 | 9.0 | 3.0 | 6.9 | 10.2 | 3.5
2004 | 2,257 | 1,671 | 586 | 5.4 | 7.9 | 2.9 | 6.3 | 9.1 | 3.4
2003 | 2,358 | 1,800 | 558 | 5.9 | 8.8 | 2.9 | 6.7 | 10.1 | 3.3
2002 | 2,137 | 1,647 | 490 | 5.5 | 8.3 | 2.6 | 6.3 | 9.5 | 3.0
2001 | 1,731 | 1,335 | 396 | 4.7 | 7.0 | 2.2 | 5.3 | 8.0 | 2.5
2000 | 1,700 | 1,348 | 352 | 4.8 | 7.4 | 2.1 | 5.4 | 8.3 | 2.4
1999 | 1,965 | 1,605 | 360 | 5.8 | 9.2 | 2.2 | 6.4 | 10.3 | 2.5
Non-Hispanic, single race^5^
American Indian and Alaska Native:
2022 | 1,641 | 1,040 | 601 | 67.8 | 86.9 | 49.1 | 69.5 | 88.8 | 50.3
2021 | 1,448 | 876 | 572 | 59.1 | 72.4 | 46.1 | 60.4 | 73.8 | 47.0
2020 | 1,076 | 642 | 434 | 44.2 | 53.7 | 35.1 | 45.1 | 54.2 | 36.4
2019 | 785 | 465 | 320 | 32.2 | 38.8 | 25.9 | 33.0 | 40.0 | 26.2
2018 | 680 | 407 | 273 | 28.1 | 34.2 | 22.2 | 29.2 | 35.5 | 23.1
Asian:
2022 | 1,184 | 909 | 275 | 5.8 | 9.3 | 2.6 | 5.5 | 8.7 | 2.5
2021 | 1,017 | 757 | 260 | 5.2 | 8.0 | 2.5 | 4.9 | 7.6 | 2.4
2020 | 990 | 753 | 237 | 5.1 | 8.1 | 2.3 | 4.9 | 7.7 | 2.2
2019 | 713 | 530 | 183 | 3.8 | 5.9 | 1.8 | 3.5 | 5.5 | 1.7
2018 | 634 | 441 | 193 | 3.4 | 4.9 | 2.0 | 3.1 | 4.6 | 1.8
Black:
2022 | 21,455 | 15,749 | 5,706 | 51.0 | 77.9 | 26.1 | 49.2 | 75.7 | 25.3
2021 | 19,944 | 14,457 | 5,487 | 47.6 | 71.8 | 25.2 | 45.8 | 69.8 | 24.4
2020 | 15,936 | 11,560 | 4,376 | 38.5 | 58.4 | 20.2 | 37.3 | 57.3 | 19.7
2019 | 11,115 | 7,968 | 3,147 | 27.0 | 40.5 | 14.7 | 26.1 | 39.9 | 14.2
2018 | 9,632 | 6,883 | 2,749 | 23.5 | 35.2 | 12.9 | 22.7 | 34.6 | 12.3
Native Hawaiian or Other Pacific Islander:
2022 | 137 | 104 | 33 | 21.5 | 32.3 | 10.5 | 20.7 | 30.9 | 10.2
2021 | 137 | 106 | 31 | 21.9 | 33.5 | 10.0 | 21.6 | 32.7 | 10.2
2020 | 91 | 70 | 21 | 14.8 | 22.6 | 6.9 | 14.6 | 22.1 | 6.9
2019 | 66 | 48 | 18 | 11.1 | 16.0 | * | 10.8 | 15.4 | 6.1
2018 | 76 | 56 | 20 | 13.0 | 19.0 | 6.9 | 13.1 | 19.0 | 7.1
White:
2022 | 70,734 | 47,595 | 23,139 | 36.0 | 48.8 | 23.4 | 36.9 | 49.2 | 24.2
2021 | 73,225 | 49,176 | 24,049 | 37.2 | 50.3 | 24.3 | 38.2 | 51.2 | 24.9
2020 | 65,270 | 43,689 | 21,581 | 33.2 | 45.0 | 21.6 | 34.5 | 46.3 | 22.5
2019 | 52,796 | 34,490 | 18,306 | 26.8 | 35.4 | 18.3 | 27.4 | 36.1 | 18.7
2018 | 52,322 | 33,679 | 18,643 | 26.5 | 34.6 | 18.6 | 27.2 | 35.3 | 19.0

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes in this report.

^1^Rates are on an annual basis per 100,000 population in specified group; see Technical Notes.

^2^Age-adjusted rates are per 100,000 U.S. standard population. For method of computation, see Technical Notes.

^3^Includes origins and races not shown separately; see Technical Notes.

^4^Includes people of Hispanic origin of any race. The Hispanic-origin category is consistent with 1997 Office of Management and Budget (OMB) standards; see Technical Notes.

^5^Only one race was reported on the death certificate. Hispanic-origin and race categories are consistent with 1997 OMB standards; see Technical Notes.

NOTE: Causes of death attributable to drug-induced mortality include International Classification of Diseases, 10th Revision codes D52.1, D59.0, D59.2, D61.1, D64.2, E06.4, E16.0, E23.1, E24.2, E27.3, E66.1, F11.1–F11.5, F11.7–F11.9, F12.1–F12.5, F12.7–F12.9, F13.1–F13.5, F13.7–F13.9, F14.1–F14.5, F14.7–F14.9, F15.1–F15.5, F15.7–F15.9, F16.1–F16.5, F16.7–F16.9, F17.3–F17.5, F17.7–F17.9, F18.1–F18.5, F18.7–F18.9, F19.1–F19.5, F19.7–F19.9, G21.1, G24.0, G25.1, G25.4, G25.6, G44.4, G62.0, G72.0, I95.2, J70.2–J70.4, K85.3, L10.5, L27.0–L27.1, M10.2, M32.0, M80.4, M81.4, M83.5, M87.1, R50.2, R78.1–R78.5, X40–X44, X60–X64, X85, and Y10–Y14.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 24 Number of deaths, death rate, and age-adjusted death rate for alcohol-induced causes, by Hispanic origin and race and sex: United States, 1999–2022

[Excludes deaths of nonresidents of the United States]

Hispanic origin and race and year | Number | | | Crude death rate^1^ | | | Age-adjusted death rate^2^
Hispanic origin and race and year | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All origins and races^3^
2022 | 51,191 | 36,426 | 14,765 | 15.4 | 22.0 | 8.8 | 13.5 | 19.5 | 7.8
2021 | 54,258 | 38,700 | 15,558 | 16.3 | 23.5 | 9.3 | 14.4 | 20.9 | 8.3
2020 | 49,061 | 35,002 | 14,059 | 14.9 | 21.6 | 8.4 | 13.1 | 19.2 | 7.5
2019 | 39,043 | 27,921 | 11,122 | 11.9 | 17.3 | 6.7 | 10.4 | 15.2 | 5.9
2018 | 37,329 | 26,820 | 10,509 | 11.4 | 16.6 | 6.3 | 9.9 | 14.7 | 5.6
2017 | 35,823 | 25,911 | 9,912 | 11.0 | 16.2 | 6.0 | 9.6 | 14.3 | 5.3
2016 | 34,865 | 25,221 | 9,644 | 10.8 | 15.9 | 5.9 | 9.5 | 14.1 | 5.2
2015 | 33,171 | 23,996 | 9,175 | 10.3 | 15.2 | 5.6 | 9.1 | 13.6 | 5.0
2014 | 30,722 | 22,389 | 8,333 | 9.6 | 14.3 | 5.1 | 8.5 | 12.9 | 4.6
2013 | 29,001 | 21,361 | 7,640 | 9.2 | 13.7 | 4.8 | 8.2 | 12.5 | 4.3
2012 | 27,762 | 20,418 | 7,344 | 8.8 | 13.2 | 4.6 | 8.0 | 12.1 | 4.2
2011 | 26,654 | 19,492 | 7,162 | 8.6 | 12.7 | 4.5 | 7.7 | 11.7 | 4.1
2010 | 25,692 | 19,038 | 6,654 | 8.3 | 12.5 | 4.2 | 7.6 | 11.7 | 3.9
2009 | 24,518 | 18,088 | 6,430 | 8.0 | 12.0 | 4.1 | 7.4 | 11.3 | 3.8
2008 | 24,189 | 18,152 | 6,037 | 8.0 | 12.1 | 3.9 | 7.4 | 11.5 | 3.6
2007 | 23,199 | 17,428 | 5,771 | 7.7 | 11.8 | 3.8 | 7.2 | 11.3 | 3.5
2006 | 22,073 | 16,472 | 5,601 | 7.4 | 11.2 | 3.7 | 7.0 | 10.9 | 3.4
2005 | 21,634 | 16,238 | 5,396 | 7.3 | 11.2 | 3.6 | 7.0 | 11.0 | 3.4
2004 | 21,081 | 15,906 | 5,175 | 7.2 | 11.1 | 3.5 | 7.0 | 11.0 | 3.3
2003 | 20,687 | 15,630 | 5,057 | 7.1 | 11.0 | 3.4 | 7.0 | 11.0 | 3.3
2002 | 20,218 | 15,272 | 4,946 | 7.0 | 10.8 | 3.4 | 6.9 | 11.0 | 3.3
2001 | 20,114 | 15,149 | 4,965 | 7.1 | 10.8 | 3.4 | 7.0 | 11.2 | 3.3
2000 | 19,643 | 14,993 | 4,650 | 7.0 | 10.9 | 3.2 | 7.0 | 11.4 | 3.2
1999 | 19,469 | 14,894 | 4,575 | 7.0 | 10.9 | 3.2 | 7.1 | 11.5 | 3.2
Hispanic^4^
2022 | 7,467 | 6,028 | 1,439 | 11.7 | 18.7 | 4.6 | 13.2 | 21.5 | 5.1
2021 | 7,533 | 6,148 | 1,385 | 12.0 | 19.4 | 4.5 | 13.6 | 22.4 | 4.9
2020 | 6,737 | 5,448 | 1,289 | 11.0 | 17.6 | 4.2 | 12.6 | 20.9 | 4.7
2019 | 5,458 | 4,442 | 1,016 | 9.0 | 14.5 | 3.4 | 10.6 | 17.8 | 3.8
2018 | 4,969 | 4,109 | 860 | 8.3 | 13.6 | 2.9 | 9.9 | 17.1 | 3.3
2017 | 4,817 | 3,934 | 883 | 8.2 | 13.2 | 3.0 | 9.9 | 16.9 | 3.5
2016 | 4,711 | 3,814 | 897 | 8.2 | 13.1 | 3.2 | 10.1 | 17.2 | 3.7
2015 | 4,474 | 3,643 | 831 | 7.9 | 12.7 | 3.0 | 9.9 | 16.9 | 3.5
2014 | 4,127 | 3,393 | 734 | 7.5 | 12.1 | 2.7 | 9.5 | 16.4 | 3.3
2013 | 3,698 | 3,034 | 664 | 6.8 | 11.0 | 2.5 | 9.0 | 15.3 | 3.1
2012 | 3,513 | 2,903 | 610 | 6.6 | 10.8 | 2.3 | 8.8 | 15.2 | 3.0
2011 | 3,445 | 2,842 | 603 | 6.6 | 10.7 | 2.4 | 9.0 | 15.6 | 3.0
2010 | 3,326 | 2,759 | 567 | 6.6 | 10.8 | 2.3 | 9.1 | 16.0 | 3.0
2009 | 3,139 | 2,618 | 521 | 6.4 | 10.4 | 2.1 | 8.9 | 15.6 | 2.9
2008 | 3,021 | 2,522 | 499 | 6.3 | 10.4 | 2.1 | 8.9 | 15.5 | 2.8
2007 | 2,977 | 2,539 | 438 | 6.4 | 10.8 | 1.9 | 9.4 | 16.8 | 2.7
2006 | 2,804 | 2,341 | 463 | 6.3 | 10.3 | 2.1 | 9.2 | 16.2 | 3.0
2005 | 2,658 | 2,265 | 393 | 6.2 | 10.3 | 1.9 | 9.1 | 16.5 | 2.6
2004 | 2,406 | 2,056 | 350 | 5.8 | 9.7 | 1.7 | 8.6 | 15.4 | 2.5
2003 | 2,422 | 2,048 | 374 | 6.0 | 10.0 | 1.9 | 9.2 | 16.4 | 2.8
2002 | 2,408 | 2,065 | 343 | 6.2 | 10.4 | 1.8 | 9.7 | 17.4 | 2.7
2001 | 2,381 | 2,026 | 355 | 6.4 | 10.6 | 2.0 | 10.1 | 18.2 | 2.9
2000 | 2,323 | 2,024 | 299 | 6.6 | 11.1 | 1.7 | 10.5 | 19.4 | 2.6
1999 | 2,184 | 1,864 | 320 | 6.4 | 10.7 | 1.9 | 10.3 | 18.6 | 3.0
Non-Hispanic, single race^5^
American Indian and Alaska Native:
2022 | 1,904 | 1,180 | 724 | 78.6 | 98.5 | 59.2 | 78.4 | 98.4 | 59.4
2021 | 2,221 | 1,377 | 844 | 90.6 | 113.8 | 68.0 | 91.7 | 116.0 | 68.7
2020 | 1,776 | 1,042 | 734 | 73.0 | 87.2 | 59.3 | 74.0 | 88.8 | 60.3
2019 | 1,315 | 785 | 530 | 54.0 | 65.5 | 42.9 | 54.0 | 65.7 | 43.3
2018 | 1,312 | 793 | 519 | 54.3 | 66.7 | 42.3 | 54.5 | 68.2 | 42.1
Asian:
2022 | 660 | 539 | 121 | 3.3 | 5.5 | 1.2 | 2.9 | 5.1 | 1.1
2021 | 638 | 504 | 134 | 3.2 | 5.3 | 1.3 | 2.9 | 5.0 | 1.2
2020 | 617 | 507 | 110 | 3.2 | 5.5 | 1.1 | 2.9 | 5.3 | 1.0
2019 | 467 | 368 | 99 | 2.5 | 4.1 | 1.0 | 2.3 | 3.9 | 0.9
2018 | 456 | 356 | 100 | 2.4 | 4.0 | 1.0 | 2.2 | 3.8 | 0.9
Black:
2022 | 4,339 | 3,025 | 1,314 | 10.3 | 15.0 | 6.0 | 9.7 | 14.5 | 5.7
2021 | 5,023 | 3,477 | 1,546 | 12.0 | 17.3 | 7.1 | 11.2 | 16.6 | 6.7
2020 | 4,329 | 3,047 | 1,282 | 10.4 | 15.4 | 5.9 | 9.7 | 15.0 | 5.5
2019 | 3,391 | 2,409 | 982 | 8.2 | 12.2 | 4.6 | 7.6 | 11.9 | 4.2
2018 | 3,143 | 2,234 | 909 | 7.7 | 11.4 | 4.3 | 7.1 | 11.2 | 3.9
Native Hawaiian or Other Pacific Islander:
2022 | 44 | 34 | 10 | 6.9 | 10.6 | * | 7.1 | 11.2 | *
2021 | 40 | 33 | 7 | 6.4 | 10.4 | * | 6.4 | 10.8 | *
2020 | 25 | 17 | 8 | 4.1 | * | * | 4.5 | * | *
2019 | 26 | 20 | 6 | 4.4 | 6.7 | * | 4.3 | 7.0 | *
2018 | 34 | 23 | 11 | 5.8 | 7.8 | * | 5.9 | 8.4 | *
White:
2022 | 36,099 | 25,139 | 10,960 | 18.4 | 25.8 | 11.1 | 14.8 | 20.5 | 9.1
2021 | 38,117 | 26,671 | 11,446 | 19.4 | 27.3 | 11.5 | 15.6 | 21.8 | 9.5
2020 | 35,033 | 24,568 | 10,465 | 17.8 | 25.3 | 10.5 | 14.3 | 20.2 | 8.7
2019 | 27,951 | 19,588 | 8,363 | 14.2 | 20.1 | 8.4 | 11.2 | 15.8 | 6.8
2018 | 26,987 | 19,001 | 7,986 | 13.7 | 19.5 | 8.0 | 10.7 | 15.3 | 6.5

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes in this report.

^1^Rates are on an annual basis per 100,000 population in specified group; see Technical Notes.

^2^Age-adjusted rates are per 100,000 U.S. standard population. For method of computation, see Technical Notes.

^3^Includes origins and races not shown separately; see Technical Notes.

^4^Includes people of Hispanic origin of any race. The Hispanic-origin category is consistent with 1997 Office of Management and Budget (OMB) standards; see Technical Notes.

^5^Only one race was reported on the death certificate. Hispanic-origin and race categories are consistent with 1997 OMB standards; see Technical Notes.

NOTE: Causes of death attributable to alcohol-induced mortality include International Classification of Diseases, 10th Revision codes E24.4, F10, G31.2, G62.1, G72.1, I42.6, K29.2, K70, K85.2, K86.0, R78.0, X45, X65, and Y15.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table 25 Number of deaths, death rate, and age-adjusted death rate for injury by firearms, by Hispanic origin and race and sex: United States, 1999–2022

[Excludes deaths of nonresidents of the United States]

Hispanic origin and race and year | Number | | | Crude death rate^1^ | | | Age-adjusted death rate^2^
Hispanic origin and race and year | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All origins and races^3^
2022 | 48,204 | 41,302 | 6,902 | 14.5 | 25.0 | 4.1 | 14.2 | 24.6 | 4.1
2021 | 48,830 | 41,866 | 6,964 | 14.7 | 25.5 | 4.2 | 14.6 | 25.3 | 4.2
2020 | 45,222 | 38,981 | 6,241 | 13.7 | 24.0 | 3.7 | 13.6 | 23.8 | 3.8
2019 | 39,707 | 34,041 | 5,666 | 12.1 | 21.1 | 3.4 | 11.9 | 20.7 | 3.4
2018 | 39,740 | 33,955 | 5,785 | 12.1 | 21.1 | 3.5 | 11.9 | 20.7 | 3.4
2017 | 39,773 | 34,062 | 5,711 | 12.2 | 21.2 | 3.5 | 12.0 | 20.9 | 3.4
2016 | 38,658 | 32,994 | 5,664 | 12.0 | 20.7 | 3.5 | 11.8 | 20.5 | 3.4
2015 | 36,252 | 31,032 | 5,220 | 11.3 | 19.6 | 3.2 | 11.1 | 19.4 | 3.2
2014 | 33,594 | 28,715 | 4,879 | 10.5 | 18.3 | 3.0 | 10.3 | 18.0 | 3.0
2013 | 33,636 | 28,794 | 4,842 | 10.6 | 18.5 | 3.0 | 10.4 | 18.3 | 3.0
2012 | 33,563 | 28,838 | 4,725 | 10.7 | 18.7 | 3.0 | 10.5 | 18.5 | 3.0
2011 | 32,351 | 27,738 | 4,613 | 10.4 | 18.1 | 2.9 | 10.2 | 18.0 | 2.9
2010 | 31,672 | 27,356 | 4,316 | 10.3 | 18.0 | 2.7 | 10.1 | 17.9 | 2.7
2009 | 31,347 | 26,921 | 4,426 | 10.2 | 17.9 | 2.8 | 10.1 | 17.8 | 2.8
2008 | 31,593 | 27,336 | 4,257 | 10.4 | 18.3 | 2.8 | 10.3 | 18.3 | 2.7
2007 | 31,224 | 27,047 | 4,177 | 10.4 | 18.3 | 2.7 | 10.3 | 18.3 | 2.7
2006 | 30,896 | 26,712 | 4,184 | 10.4 | 18.2 | 2.8 | 10.3 | 18.2 | 2.7
2005 | 30,694 | 26,657 | 4,037 | 10.4 | 18.4 | 2.7 | 10.3 | 18.5 | 2.7
2004 | 29,569 | 25,498 | 4,071 | 10.1 | 17.7 | 2.7 | 10.0 | 17.9 | 2.7
2003 | 30,136 | 26,124 | 4,012 | 10.4 | 18.3 | 2.7 | 10.3 | 18.5 | 2.7
2002 | 30,242 | 26,098 | 4,144 | 10.5 | 18.5 | 2.8 | 10.5 | 18.7 | 2.8
2001 | 29,573 | 25,480 | 4,093 | 10.4 | 18.2 | 2.8 | 10.3 | 18.5 | 2.8
2000 | 28,663 | 24,582 | 4,081 | 10.2 | 17.8 | 2.8 | 10.2 | 18.1 | 2.8
1999 | 28,874 | 24,700 | 4,174 | 10.3 | 18.1 | 2.9 | 10.3 | 18.4 | 2.9
Hispanic^4^
2022 | 5,853 | 5,081 | 772 | 9.2 | 15.7 | 2.5 | 8.9 | 15.2 | 2.4
2021 | 5,741 | 5,014 | 727 | 9.2 | 15.8 | 2.4 | 8.9 | 15.3 | 2.3
2020 | 5,003 | 4,395 | 608 | 8.2 | 14.2 | 2.0 | 7.9 | 13.8 | 1.9
2019 | 4,058 | 3,503 | 555 | 6.7 | 11.5 | 1.8 | 6.6 | 11.2 | 1.9
2018 | 4,018 | 3,521 | 497 | 6.7 | 11.6 | 1.7 | 6.6 | 11.6 | 1.7
2017 | 3,884 | 3,369 | 515 | 6.6 | 11.3 | 1.8 | 6.5 | 11.1 | 1.8
2016 | 3,771 | 3,316 | 455 | 6.6 | 11.4 | 1.6 | 6.4 | 11.2 | 1.6
2015 | 3,332 | 2,912 | 420 | 5.9 | 10.2 | 1.5 | 5.8 | 10.1 | 1.5
2014 | 3,010 | 2,630 | 380 | 5.4 | 9.4 | 1.4 | 5.4 | 9.4 | 1.4
2013 | 2,951 | 2,595 | 356 | 5.5 | 9.4 | 1.3 | 5.4 | 9.4 | 1.3
2012 | 3,061 | 2,724 | 337 | 5.8 | 10.1 | 1.3 | 5.7 | 10.1 | 1.3
2011 | 2,947 | 2,608 | 339 | 5.7 | 9.9 | 1.3 | 5.6 | 9.8 | 1.3
2010 | 3,008 | 2,694 | 314 | 6.0 | 10.5 | 1.3 | 5.9 | 10.5 | 1.3
2009 | 3,202 | 2,867 | 335 | 6.5 | 11.4 | 1.4 | 6.4 | 11.4 | 1.4
2008 | 3,256 | 2,912 | 344 | 6.8 | 12.0 | 1.5 | 6.6 | 11.7 | 1.5
2007 | 3,492 | 3,155 | 337 | 7.6 | 13.4 | 1.5 | 7.2 | 12.9 | 1.5
2006 | 3,464 | 3,142 | 322 | 7.8 | 13.8 | 1.5 | 7.3 | 12.8 | 1.4
2005 | 3,469 | 3,144 | 325 | 8.1 | 14.3 | 1.5 | 7.6 | 13.4 | 1.5
2004 | 3,278 | 2,973 | 305 | 7.9 | 14.0 | 1.5 | 7.5 | 13.2 | 1.5
2003 | 3,319 | 2,998 | 321 | 8.3 | 14.6 | 1.6 | 7.8 | 13.7 | 1.6
2002 | 3,143 | 2,834 | 309 | 8.1 | 14.3 | 1.6 | 7.7 | 13.6 | 1.6
2001 | 3,087 | 2,774 | 313 | 8.3 | 14.5 | 1.7 | 7.8 | 13.7 | 1.7
2000 | 2,891 | 2,582 | 309 | 8.2 | 14.2 | 1.8 | 7.8 | 13.6 | 1.8
1999 | 2,878 | 2,549 | 329 | 8.5 | 14.6 | 2.0 | 8.2 | 14.2 | 2.0
Non-Hispanic, single race^5^
American Indian and Alaska Native:
2022 | 530 | 452 | 78 | 21.9 | 37.7 | 6.4 | 22.2 | 37.7 | 6.7
2021 | 466 | 390 | 76 | 19.0 | 32.2 | 6.1 | 19.1 | 32.1 | 6.3
2020 | 449 | 381 | 68 | 18.5 | 31.9 | 5.5 | 18.1 | 31.2 | 5.3
2019 | 336 | 272 | 64 | 13.8 | 22.7 | 5.2 | 13.8 | 22.5 | 5.3
2018 | 361 | 298 | 63 | 14.9 | 25.0 | 5.1 | 15 | 24.8 | 5.4
Asian:
2022 | 583 | 474 | 109 | 2.9 | 4.9 | 1.0 | 2.7 | 4.6 | 1.0
2021 | 576 | 469 | 107 | 2.9 | 5.0 | 1.0 | 2.9 | 4.8 | 1.0
2020 | 516 | 435 | 81 | 2.7 | 4.7 | 0.8 | 2.6 | 4.5 | 0.8
2019 | 513 | 424 | 89 | 2.7 | 4.7 | 0.9 | 2.5 | 4.4 | 0.8
2018 | 492 | 396 | 96 | 2.6 | 4.4 | 1.0 | 2.5 | 4.2 | 1.0
Black:
2022 | 14,203 | 12,410 | 1,793 | 33.8 | 61.4 | 8.2 | 33.2 | 59.0 | 8.3
2021 | 15,290 | 13,349 | 1,941 | 36.5 | 66.3 | 8.9 | 36.0 | 64.0 | 9.0
2020 | 13,974 | 12,416 | 1,558 | 33.7 | 62.7 | 7.2 | 33.1 | 59.9 | 7.3
2019 | 10,288 | 9,198 | 1,090 | 25.0 | 46.8 | 5.1 | 24.5 | 44.8 | 5.1
2018 | 9,713 | 8,567 | 1,146 | 23.7 | 43.8 | 5.4 | 23.2 | 42.0 | 5.4
Native Hawaiian or Other Pacific Islander:
2022 | 65 | 58 | 7 | 10.2 | 18.0 | * | 9.8 | 17.1 | *
2021 | 68 | 63 | 5 | 10.9 | 19.9 | * | 10.4 | 18.9 | *
2020 | 58 | 52 | 6 | 9.5 | 16.8 | * | 9.1 | 15.7 | *
2019 | 54 | 45 | 9 | 9.1 | 15.0 | * | 8.6 | 14.0 | *
2018 | 54 | 48 | 6 | 9.2 | 16.3 | * | 8.8 | 15.6 | *
White:
2022 | 26,323 | 22,285 | 4,038 | 13.4 | 22.9 | 4.1 | 12.2 | 20.7 | 3.9
2021 | 26,054 | 22,068 | 3,986 | 13.2 | 22.6 | 4.0 | 12.3 | 21.0 | 3.9
2020 | 24,664 | 20,838 | 3,826 | 12.5 | 21.5 | 3.8 | 11.6 | 19.9 | 3.7
2019 | 23,964 | 20,173 | 3,791 | 12.1 | 20.7 | 3.8 | 11.1 | 19.0 | 3.6
2018 | 24,643 | 20,745 | 3,898 | 12.5 | 21.3 | 3.9 | 11.4 | 19.5 | 3.7

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes in this report.

^1^Rates are on an annual basis per 100,000 population in specified group; see Technical Notes.^2^Age-adjusted rates are per 100,000 U.S. standard population. For method of computation, see Technical Notes.

^3^Includes origins and races not shown separately; see Technical Notes.

^4^Includes people of Hispanic origin of any race. The Hispanic origin category is consistent with 1997 Office of Management and Budget (OMB) standards; see Technical Notes.

^5^Only one race was reported on the death certificate. Hispanic-origin and race categories are consistent with 1997 OMB standards; see Technical Notes.

NOTE: Causes of death attributable to injury by firearms include International Classification of Diseases, 10th Revision codes U01.4, W32–W34, X72–X74, X93–X95, Y22–Y24, and Y35.0.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Mortality data on specific demographic and medical characteristics cover all 50 states and the District of Columbia. Measures of mortality in this report include the number of deaths; crude, age-specific, and age-adjusted death rates; infant, neonatal, postneonatal, and maternal mortality rates; life expectancy; and rate ratios. Changes in death rates in 2022 compared with 2021 and differences in death rates across demographic groups in 2022 were tested for statistical significance. Unless otherwise specified, reported differences are statistically significant. Additional information on these statistical methods, random variation and relative standard error, the computation of derived statistics and rates, population denominators, and the definition of terms are presented in Technical Notes.

In accordance with the revised standards issued by OMB in 1997, the 2003 revision of the U.S. Standard Certificate of Death provided for the reporting of more than one race (multiple races) and increased the race categories from four to five by separating the Asian and Pacific Islander groups (7,8). Starting in 2018, all 50 states and the District of Columbia reported deaths using the 2003 revision for the entire year.

The race and Hispanic-origin groups in this report follow the 1997 standards and differ from the race categories used in reports for data years before 2018 (8,10,15). The categories include Hispanic, single-race American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native), single-race Asian non-Hispanic (subsequently, Asian), single-race Black or African American non-Hispanic (subsequently, Black), single-race Native Hawaiian or Other Pacific Islander non-Hispanic (subsequently, Native Hawaiian or Other Pacific Islander), and single-race White non-Hispanic (subsequently, White). For brevity, text references to race refer to single race in this report. Because the number of deaths reported with more than one race in 2022 is relatively small (0.6%), these deaths are included in totals but are shown separately in only one report table (Table 2). Some comparisons between race and ethnicity groups in this report are limited to the following groups based on population size: American Indian and Alaska Native, Asian, Black, Hispanic, and White.

Data presented in this report by the revised Hispanic-origin and race categories for 2018–2022 are not completely comparable with data by bridged-race shown in earlier reports, and comparisons should be made with this consideration. The Hispanic-origin category is a separate item on the death certificate and was not affected by the revised standards; as a result, data by Hispanic origin for 2022 and earlier years are comparable.

Death rates by race and ethnicity for the American Indian and Alaska Native, Asian, Hispanic, and Native Hawaiian or Other Pacific Islander populations are affected by inconsistencies in reporting Hispanic origin and race on death certificates as compared with censuses and surveys (16). Death rates for the American Indian and Alaska Native population are underestimated by about 33% due to misclassification (16). Death rates for the Asian and Hispanic populations are underestimated by about 3.0% (16). This should be considered when making rate comparisons across racial and ethnic groups. At this time, information about the prevalence of misclassification for the Native Hawaiian or Other Pacific Islander population is not available.

To maintain consistency with data reported by the jurisdictions and data in the mortality data file, numbers of deaths and death rates in this report are not adjusted for misclassification of race and ethnicity unless otherwise indicated. Specifically, Tables 4 and 5 present life expectancies by Hispanic origin and race that are produced using methods based on death rates adjusted for Hispanic origin and race misclassification on death certificates. For additional detail, see Quality of race and Hispanic-origin data in Technical Notes.

The population data used to calculate death rates for 2022 shown in this report are estimated as of July 1, 2022, based on the Blended Base produced by the U.S. Census Bureau (Technical Notes), and are available from the CDC WONDER website: https://wonder.cdc.gov/single-race-population.html (17).

Data presented in this report and other mortality tabulations are available from the National Vital Statistics System website: https://www.cdc.gov/nchs/deaths.htm. The availability of mortality microdata is described in Technical Notes.

## Results and Discussion

### Deaths and death rates

In 2022, a total of 3,279,857 resident deaths were registered in the United States—184,374 fewer deaths than in 2021. The crude death rate for 2022 (984.1 deaths per 100,000 population) was 5.7% lower than the 2021 rate (1,043.8) (Tables A, 1, 2, 6, 8, and 10).

Table A Percent change in death rates and age-adjusted death rates in 2022 from 2021, by age, Hispanic origin and race, and sex: United States

[Based on death rates on an annual basis per 100,000 population and age-adjusted rates per 100,000 U.S. standard population; see Technical Notes in this report. Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards; see Technical Notes. Data for some Hispanic-origin or race categories should be interpreted with caution because of inconsistencies in reporting these items on death certificates and surveys; see Technical Notes]

Age group | Total^1^ | | | Hispanic^2^ | | | Non-Hispanic, single race^3^
Age group | Total^1^ | | | Hispanic^2^ | | | American Indian and Alaska Native | | | Asian | | | Black | | | Native Hawaiian or Other Pacific Islander | | | White
Age group | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female | Both sexes | Male | Female
All ages
Crude rate | -5.7 | -7.0 | -4.3 | -14.1 | -15.8 | -11.7 | -11.3 | -12.7 | -9.7 | -5.9 | -7.7 | -3.9 | -8.9 | -8.5 | -9.3 | -13.4 | -16.6 | -9.4 | -3.7 | -5.0 | -2.1
Age-adjusted rate | -9.2 | -8.9 | -9.2 | -15.2 | -15.4 | -14.5 | -14.5 | -15.5 | -13.8 | -9.6 | -9.6 | -9.2 | -10.3 | -8.5 | -11.8 | -15.4 | -17.6 | -12.5 | -8.0 | -7.9 | -7.8
Younger than 1^4^ | -0.1 | 0.8 | -1.4 | 1.1 | 2.2 | -0.3 | 15.3 | 22.6 | 6.9 | -6.7 | -5.3 | -8.6 | -5.5 | -5.0 | -6.2 | 30.0 | 6.4 | 76.9 | 1.6 | 2.8 | 0.1
1–4 | 12.0 | 14.8 | 8.3 | 9.4 | 13.6 | 5.0 | 26.3 | 2.1 | 65.1 | 1.4 | 10.3 | -6.9 | 5.6 | 11.7 | -1.7 | * | * | * | 16.0 | 17.6 | 14.1
5–14 | 7.0 | 4.3 | 9.0 | 4.8 | 6.6 | 2.7 | 39.3 | 56.4 | 22.9 | -1.2 | -3.1 | 0.0 | 0.8 | -3.5 | 8.1 | * | * | * | 9.4 | 6.8 | 13.0
15–24 | -10.6 | -11.0 | -10.1 | -8.9 | -8.4 | -11.3 | -5.7 | -4.6 | -7.9 | -13.0 | -13.3 | -13.3 | -10.4 | -9.5 | -13.2 | -27.9 | -24.6 | -36.9 | -11.2 | -12.8 | -7.7
25–34 | -9.6 | -9.9 | -9.8 | -8.7 | -7.7 | -12.5 | -6.3 | -7.8 | -3.9 | -7.3 | -7.6 | -7.2 | -10.7 | -10.2 | -12.6 | -21.1 | -24.7 | -12.2 | -9.7 | -10.8 | -8.1
35–44 | -11.3 | -11.0 | -12.2 | -16.9 | -16.4 | -18.8 | -10.3 | -7.2 | -15.6 | -9.7 | -12.4 | -5.1 | -11.3 | -10.5 | -13.2 | -28.4 | -27.0 | -30.9 | -9.5 | -9.3 | -10.3
45–54 | -14.6 | -15.3 | -13.8 | -24.3 | -25.4 | -22.4 | -15.8 | -17.0 | -14.4 | -12.5 | -14.1 | -10.1 | -15.2 | -14.4 | -16.6 | -27.8 | -32.8 | -20.2 | -11.7 | -12.5 | -10.6
55–64 | -11.2 | -12.0 | -10.1 | -24.7 | -25.3 | -23.7 | -17.2 | -20.2 | -12.9 | -14.9 | -16.0 | -13.5 | -12.7 | -11.9 | -13.8 | -15.3 | -15.0 | -15.8 | -8.2 | -9.4 | -6.6
65–74 | -8.0 | -8.3 | -7.5 | -19.6 | -20.0 | -19.1 | -15.9 | -15.1 | -16.7 | -11.0 | -10.8 | -11.4 | -10.0 | -8.5 | -11.6 | -12.9 | -18.9 | -5.4 | -6.1 | -6.9 | -5.1
75–84 | -8.0 | -8.4 | -7.6 | -14.9 | -16.1 | -13.6 | -16.3 | -19.9 | -12.8 | -9.3 | -10.5 | -7.7 | -9.6 | -7.3 | -11.4 | -5.7 | -5.7 | -5.8 | -7.1 | -7.7 | -6.5
85 and older | -8.6 | -6.1 | -9.9 | -7.1 | -4.2 | -8.5 | -19.2 | -21.1 | -18.0 | -7.4 | -4.8 | -9.0 | -7.8 | -3.3 | -9.7 | -16.9 | -14.5 | -18.5 | -8.7 | -6.3 | -10.0

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.^1^Includes deaths with origin not stated, origin not classifiable, and two or more races reported; see Technical Notes.^2^Includes persons of Hispanic origin of any race; see Technical Notes.^3^Only one race was reported on the death certificate; see Technical Notes.^4^Death rates for “Younger than 1” (based on population estimates) differ from infant mortality rates (based on live births); see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

The age-adjusted death rate in 2022 was 798.8 deaths per 100,000 U.S. standard population—9.2% lower than the rate of 879.7 in 2021 (Tables A and 1). The age-adjusted death rates decreased for males (8.9%) and females (9.2%). Age-adjusted death rates should be viewed as relative indexes rather than as actual measures of mortality risk. They are constructs that show what the level of mortality would be if no changes occurred in the age composition of the population from year to year. (For a discussion of age-adjusted death rates, see Technical Notes.) Thus, age-adjusted death rates are better indicators than unadjusted (crude) death rates for examining changes in the risk of death over a period of time when the age distribution of the population is changing. Age-adjusted death rates are also better indicators of relative risk when comparing mortality across geographic areas or between sex or race and ethnicity subgroups of the population that have different age distributions; see Technical Notes. Since 1980, the age-adjusted death rate decreased significantly every year except for 1983, 1985, 1988, 1993, 1999, 2005, 2010, 2013, 2015, 2017, 2020, and 2021 (Figure 1) (14).

Figure 1 Crude and age-adjusted death rates: United States, 1960–2022

NOTE: Crude death rates are on an annual basis per 100,000 population; age-adjusted rates are per 100,000 U.S. standard populat

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 1 is a line graph showing crude and age-adjusted death rates for the resident population of the United States from 1960 through 2022.

#### Death rates by Hispanic origin and race

In 2022, age-adjusted death rates by ethnicity and race groups (Table 1) were:

- Hispanic population: 614.7 deaths per 100,000 U.S. standard population
- American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native) population: 947.9
- Asian non-Hispanic (subsequently, Asian) population: 417.5
- Black non-Hispanic (subsequently, Black) population: 1,002.8
- Native Hawaiian or Other Pacific Islander non-Hispanic (subsequently, Native Hawaiian or Other Pacific Islander) population: 782.0
- White non-Hispanic (subsequently, White) population: 822.2

In 2022, the age-adjusted death rate for the American Indian and Alaska Native population was 1.2 times that for the White population. The rate for the Black population was 1.2 times that for the White population. The rate for the White population was 2.0 times the rate for the Asian population, 1.1 times the rate for Native Hawaiian or Other Pacific Islander population, and 1.3 times the rate for the Hispanic population (Table B).

From 2021 to 2022, the age-adjusted rate decreased 15.4% (from 924.3 to 782.0) for the Native Hawaiian or Other Pacific Islander population, 15.2% (from 724.7 to 614.7) for the Hispanic population, 14.5% (from 1,109.2 to 947.9) for the American Indian and Alaska Native population, 10.3% (from 1,118.0 to 1,002.8) for the Black population, 9.6% (461.7 to 417.5) for the Asian population, and 8.0% (893.9 to 822.2) for the White population (Tables A and 1).

From 2021 to 2022, the age-adjusted death rate decreased 17.6% for Native Hawaiian or Other Pacific Islander males, 15.5% for American Indian and Alaska Native males, 15.4% for Hispanic males, 14.5% for Hispanic females, 13.8% for American Indian and Alaska Native females, 12.5% for Native Hawaiian or Other Pacific Islander females, 11.8% for Black females, 9.6% for Asian males, 9.2% for Asian females, 8.5% for Black males, 7.9% for White males, and 7.8% for White females (Tables A and 1).

Hispanic subgroups—Mortality data for 2022 by specified Hispanic subgroup for the United States are presented in Table 3. Hispanic subgroups shown in the table include Central American, Cuban, Dominican, Mexican, Puerto Rican, South American, and Other Hispanic populations.

In 2022, age-adjusted rates among the Hispanic subgroups ranged from a low of 344.9 for the South American population to a high of 688.1 for the Puerto Rican population. Differences between subgroups are likely a function of large variation in age-specific death rates for some of the Hispanic subgroups, reflecting their relatively small population sizes. Data aggregated over several years confirm differences among the Hispanic subgroups (16).

#### Death rates by age and sex

For the total population, age-specific death rates increased significantly from 2021 to 2022 for age groups 1–4 and 5–14 and decreased for age groups 15–24, 25–34, 35–44, 45–54, 55–64, 65–74, 75–84, and 85 and older (Tables 6 and 8; Figure 2). The rate for younger than 1 year did not change significantly.

Figure 2 Death rate, by age and sex: United States, 1955–2022

^1^Rates are based on population estimates, which differ from infant mortality rates (based on live births); see Figure 5 in this report for infant mortality rates and for further discussion of the difference.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 2 is a line graph showing age-specific death rates by sex for the resident population of the United States from 1955 through 2022 for the following age groups: younger than 1 year, 1 through 4, 5 through 14, 15 through 24, 25 through 34, 35 through 44, 45 through 54, 55 through 64, 65 through 74, 75 through 84, and 85 and older.

The age-adjusted death rate for males was 1.4 times the rate for females in 2022 (Table B). The male-to-female death rate ratio was unchanged from the ratio in 2021.

Death rates for males increased significantly for age group 1–4 and decreased for age groups 15–24, 25–34, 35–44, 45–54, 55–64, 65–74, 75–84, and 85 and older. Changes in rates for males younger than 1 and ages 5–14 were not statistically significant. Death rates for females increased significantly for age groups 1–4 and 5–14 and decreased for age groups 15–24, 25–34, 35–44, 45–54, 55–64, 65–74, 75–84, and 85 and older. The rate for females younger than 1 did not change significantly.

Race and ethnicity by sex—For the total Hispanic population, Hispanic males, and Hispanic females, age-specific death rates decreased from 2021 to 2022 for age groups 15–24, 25–34, 35–44, 45–54, 55–64, 65–74, 75–84, and 85 and older.

For the total, male, and female American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native) populations, age-specific death rates decreased from 2021 to 2022 for age groups 35–44, 45–54, 55–64, 65–74, 75–84, and 85 and older. For the total and male American Indian and Alaska Native populations, the rates increased for age group 5–14.

For the total Asian non-Hispanic (subsequently, Asian) population, age-specific rates decreased from 2021 to 2022 for age groups 15–24, 25–34, 35–44, 45–54, 55–64, 65–74, 75–84, and 85 and older. For Asian males, rates decreased for age groups 15–24, 35–44, 45–54, 55–64, 65–74, 75–84, and 85 and older. For Asian females, rates decreased for age groups 45–54, 55–64, 65–74, 75–84, and 85 and older.

For the total, male, and female Black non-Hispanic (subsequently, Black) populations, age-specific death rates decreased from 2021 to 2022 for age groups younger than 1, 15–24, 25–34, 35–44, 45–54, 55–64, 65–74, 75–84, and 85 and older.

For the total Native Hawaiian or Other Pacific Islander non-Hispanic (subsequently, Native Hawaiian or Other Pacific Islander) population, age-specific death rates decreased for age groups 15–24, 25–34, 35–44, 45–54, 55–64, 65–74, and 85 and older. For Native Hawaiian or Other Pacific Islander males, rates decreased for age groups 25–34, 35–44, 45–54, 55–65, and 65–74. For Native Hawaiian or Other Pacific Islander females, rates increased for younger than 1 year and decreased for age groups 35–44, 45–54, 55–64, and 85 and older.

For the total, male, and female White non-Hispanic (subsequently, White) populations, age-specific death rates decreased from 2021 to 2022 for age groups 15–24, 25–34, 35–44, 45–54, 55–64, 65–74, 75–84, and 85 and older. For the total and female White populations, the rates increased for age groups 1–4 and 5–14 and for White males, the rate increased for age group 1–4 (Tables A and 2).

Other observed changes from 2021 to 2022 in age-specific rates by race and ethnicity and sex were not statistically significant.

### Expectation of life at birth and at specified ages

Life expectancy at birth represents the average number of years that a group of infants would live if the group was to experience throughout life the age-specific death rates present in the year of birth.

Life table data shown in this report for 2010–2022 are based on a revised methodology first presented with final data reported for 2008. The life table methodology was revised by changing the smoothing technique used to estimate the life table functions at the oldest ages. This revision improves on the methodologies used previously; see Technical Notes.

The methods used to produce life expectancies by Hispanic origin and race are based on death rates adjusted for Hispanic-origin and race misclassification on death certificates (Technical Notes). As noted in the Methods section, the age-specific and age-adjusted death rates shown in this report (with the exception of Table IV) are not adjusted for misclassification of Hispanic origin and race on death certificates. For further information on the effects of Hispanic origin and race misclassification on death rates, see Technical Notes.

Life tables were generated for both sexes and by each sex for the following populations:

- Total United States
- Hispanic
- American Indian and Alaska Native non-Hispanic
- Asian non-Hispanic
- Black non-Hispanic
- White non-Hispanic

In 2022, life expectancy for the total population (77.5 years) was 1.1 years higher than in 2021. This increase followed the two largest single-year decreases in life expectancy (1.8 years in 2020 and 0.6 year in 2021) since 1943 (Tables 4 and 5). The increase in life expectancy was mostly due to the decrease in deaths from COVID-19. Before the COVID-19 pandemic, the general trend in U.S. life expectancy had been one of improvement since 1900. In 2022, life expectancy for males (74.8 years) was 1.3 years higher than in 2021. Life expectancy for females (80.2 years) was 0.9 year higher than in 2021. From 1900 through the late 1970s, the gap in life expectancy between the sexes widened from 2.0 to 7.8 years (3). The gap between sexes has narrowed since its peak in the 1970s (Figure 3 and Table 5). In 2022, the difference in life expectancy between males and females was 5.4 years, a decrease of 0.4 year from 2021.

Figure 3 Life expectancy at birth, by sex: United States, 1970–2022

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 3 is a line graph showing life expectancy at birth in the United States from 1970 through 2022 for both sexes and male and female.

Life expectancy figures for the Hispanic, Black non-Hispanic (subsequently, Black), and White non-Hispanic (subsequently, White) populations have been available starting with data for 2006. Before 2006, life tables were produced for the Black and White populations, regardless of Hispanic origin (18). Life tables for the American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native) and Asian non-Hispanic (subsequently, Asian) populations were added to the Life Table Program beginning with data for 2019 (19).

Life expectancy for the American Indian and Alaska Native population increased 2.2 years (from 65.6 years in 2021 to 67.8 in 2022).

Life expectancy for the Hispanic population increased by 2.2 years (from 77.8 years in 2021 to 80.0 in 2022) (Table 5). The difference in life expectancy between the Hispanic and White populations increased 1.4 years from 1.1 years in 2021 to 2.5 years in 2022.

Life expectancy increased by 1.6 years for the Black population (from 71.2 years in 2021 to 72.8 in 2022). The difference in life expectancy between the White and Black populations decreased 0.8 year from 5.5 years in 2021 to 4.7 years in 2022 (Table 5).

Life expectancy increased by 0.9 year for the Asian population (from 83.5 years in 2021 to 84.4 in 2022) (Table 5).

Life expectancy increased by 0.8 year for the White population (from 76.7 years in 2021 to 77.5 in 2022) (Table 5).

Among the 10 major race–ethnicity–sex groups in 2022, Asian females had the highest life expectancy at birth (86.3 years), followed by Hispanic females (82.8), Asian males (82.3), White females (80.1), Hispanic males (77.0), Black females (76.5), White males (75.1), American Indian and Alaska Native females (71.3), Black males (69.1), and American Indian and Alaska Native males (64.5) (Tables 4 and 5).

Life tables shown in this report may be used to compare life expectancies at selected ages from birth to 100 years. For example, based on mortality experienced in 2022 for the total population, a person age 50 could expect to live an average of 30.9 more years, for a total of 80.9 years. A person age 65 could expect to live an average of 18.9 more years, for a total of 83.9 years, and a person age 85 could expect to live an average of 6.4 more years, for a total of 91.4 years (Table 4). Life expectancy increased at ages from birth through age 85 and was either unchanged or decreased for age 90 and older from 2021 to 2022 (3).

### Leading causes of death

The 15 leading causes of death in 2022 accounted for 79.1% of all deaths in the United States (Tables B and 6). In 2022, the 15 leading causes of death remained the same as in 2021, although some changed ranks. Heart disease and cancer remained the top two leading causes in 2022. Of the remaining leading causes in 2022, six causes changed rank. Unintentional injuries, the 4th leading cause in 2021, became the 3rd leading cause in 2022. COVID-19, the 3rd leading cause in 2021, became the 4th. Kidney disease, the 10th leading cause in 2021, became the 9th. Chronic liver disease and cirrhosis, the 9th leading cause in 2021, became the 10th. Influenza and pneumonia, the 13th leading cause in 2021, became the 12th. Hypertension, the 12th leading cause in 2021, became the 13th. Causes of death are ranked according to the number of deaths; for ranking procedures, see Technical Notes. By rank, the 15 leading causes of death in 2022 were:

1. Diseases of heart (heart disease)
2. Malignant neoplasms (cancer)
3. Accidents (unintentional injuries)
4. COVID-19
5. Cerebrovascular diseases (stroke)
6. Chronic lower respiratory diseases
7. Alzheimer disease
8. Diabetes mellitus (diabetes)
9. Nephritis, nephrotic syndrome and nephrosis (kidney disease)
10. Chronic liver disease and cirrhosis
11. Intentional self-harm (suicide)
12. Influenza and pneumonia
13. Essential hypertension and hypertensive renal disease (hypertension)
14. Septicemia
15. Parkinson disease

Table B Number of deaths, percentage of total deaths, death rate, and age-adjusted death rate for 2022, percent change in age-adjusted death rates in 2022 from 2021, and ratio of age-adjusted death rates, by sex and by Hispanic origin and race for the 15 leading causes of death for the total population in 2022: United States

[Crude death rates on an annual basis per 100,000 population; age-adjusted rates per 100,000 U.S. standard population; see Technical Notes in this report. An asterisk (*) preceding a cause-of-death code indicates that the code is not included in the International Classification of Diseases, 10th Revision (ICD–10); see Technical Notes. Hispanic-origin and race categories are consistent with 1997 Office of Management and Budget standards]

Rank^1^ | Cause of death (based on ICD–10) | Number | Percent of total deaths, 2022^2^ | Crude death rate, 2022 | Age-adjusted death rate
Rank^1^ | Cause of death (based on ICD–10) | Number | Percent of total deaths, 2022^2^ | Crude death rate, 2022 | 2022 | Percent change from 2021 to 2022 | Ratio
Rank^1^ | Cause of death (based on ICD–10) | Number | Percent of total deaths, 2022^2^ | Crude death rate, 2022 | 2022 | Percent change from 2021 to 2022 | Male to female | Non-Hispanic, single race^3^ | | | | White, non-Hispanic^3^ to Hispanic^4^
Rank^1^ | Cause of death (based on ICD–10) | Number | Percent of total deaths, 2022^2^ | Crude death rate, 2022 | 2022 | Percent change from 2021 to 2022 | Male to female | American Indian and Alaska Native to White | Black to White | White to Asian | White to Native Hawaiian or Other Pacific Islander | White, non-Hispanic^3^ to Hispanic^4^
… | All causes | 3,279,857 | 100.0 | 984.1 | 798.8 | -9.2 | 1.4 | 1.2 | 1.2 | 2.0 | 1.1 | 1.3
1 | Diseases of heart(I00–I09,I11,I13,I20–I51) | 702,880 | 21.4 | 210.9 | 167.2 | -3.8 | 1.6 | 0.9 | 1.3 | 2.1 | 1.0 | 1.5
2 | Malignant neoplasms(C00–C97) | 608,371 | 18.5 | 182.5 | 142.3 | -2.9 | 1.3 | 0.8 | 1.1 | 1.7 | 1.1 | 1.4
3 | Accidents (unintentional injuries)(V01–X59,Y85–Y86) | 227,039 | 6.9 | 68.1 | 64.0 | -1.1 | 2.3 | 1.9 | 1.2 | 3.6 | 1.4 | 1.4
4 | COVID-19(U07.1) | 186,552 | 5.7 | 56.0 | 44.5 | -57.3 | 1.6 | 1.5 | 1.2 | 1.7 | 0.9 | 0.9
5 | Cerebrovascular diseases(I60–I69) | 165,393 | 5.0 | 49.6 | 39.5 | -3.9 | 1.1 | 0.8 | 1.5 | 1.3 | 0.7 | 1.1
6 | Chronic lower respiratory diseases(J40–J47) | 147,382 | 4.5 | 44.2 | 34.3 | -1.2 | 1.1 | 0.7 | 0.7 | 4.7 | 2.0 | 2.8
7 | Alzheimer disease(G30) | 120,122 | 3.7 | 36.0 | 28.9 | -6.8 | 0.7 | 0.5 | 0.9 | 1.9 | 1.5 | 1.1
8 | Diabetes mellitus(E10–E14) | 101,209 | 3.1 | 30.4 | 24.1 | -5.1 | 1.6 | 2.2 | 2.0 | 1.2 | 0.4 | 0.8
9 | Nephritis, nephrotic syndrome and nephrosis(N00–N07,N17–N19,N25–N27) | 57,937 | 1.8 | 17.4 | 13.8 | 1.5 | 1.4 | 1.4 | 2.2 | 1.3 | 0.6 | 1.0
10 | Chronic liver disease and cirrhosis(K70,K73–K74) | 54,803 | 1.7 | 16.4 | 13.8 | -4.8 | 1.8 | 4.4 | 0.6 | 3.6 | 2.0 | 0.9
11 | Intentional self-harm (suicide)(*U03,X60–X84,Y87.0) | 49,476 | 1.5 | 14.8 | 14.2 | 0.7 | 3.9 | 1.5 | 0.5 | 2.6 | 1.2 | 2.2
12 | Influenza and pneumonia(J09–J18) | 47,052 | 1.4 | 14.1 | 11.3 | 7.6 | 1.4 | 1.4 | 1.1 | 1.4 | 1.1 | 1.2
13 | Essential hypertension and hypertensive renal disease (I10,I12,I15) | 43,293 | 1.3 | 13.0 | 10.3 | -3.7 | 1.2 | 1.0 | 2.0 | 1.1 | 0.8 | 1.0
14 | Septicemia(A40–A41) | 42,261 | 1.3 | 12.7 | 10.1 | -1.0 | 1.3 | 1.3 | 1.7 | 2.2 | 0.9 | 1.3
15 | Parkinson disease(G20–G21) | 39,915 | 1.2 | 12.0 | 9.5 | -3.1 | 2.3 | 0.4 | 0.5 | 1.8 | * | 1.6
… | All other causes(residual) | 686,172 | 20.9 | 205.9 | … | … | … | … | … | … | … | …

* Estimate does not meet National Center for Health Statistics standards of reliability; see Technical Notes.

… Category not applicable.

^1^Based on number of deaths; see Technical Notes.

^2^Percentages may not add to 100 due to rounding.

^3^Includes only one race reported on the death certificate; see Technical Notes.

^4^Includes people of Hispanic origin of any race; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Death rates vary greatly by age. As a result, the shifting age distribution of a population can significantly influence changes in crude death rates over time. Age-adjusted death rates, in contrast, eliminate the influence of such differences in the population age structure. Consequently, while causes of death are ranked according to the number of deaths, age-adjusted death rates are used to depict trends for leading causes of death in this report because they are better than crude rates for showing changes in mortality over time and among causes of death (Figure 4; Tables B and 6).

Figure 4 Age-adjusted death rate for selected leading causes of death: United States, 1958–2022

NOTES: ICD is the International Classification of Diseases. Circled numbers indicate ranking of conditions as leading causes of death in 2022.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 4 is a line graph showing age-adjusted death rates for selected causes of death in the United States from 1958 through 2022.

From 2021 through 2022, age-adjusted death rates decreased significantly for 11 of the 15 leading causes of death and increased for 2 of the 15 leading causes (Tables B and 6). The rate for the top leading cause of death, heart disease, decreased 3.8% in 2022 from 2021 (Figure 4; Tables B and 6) (14). The rate for the second leading cause of death, cancer, decreased 2.9% from 2021 to 2022. Deaths from these two diseases combined accounted for 40.0% of deaths in the United States in 2022.

Unintentional injuries, the third leading cause of death in 2022, accounted for 6.9% of deaths in the United States. The age-adjusted death rate for unintentional injuries decreased 1.1% from 2021 (64.7) to 2022 (64.0).

COVID-19, the fourth leading cause of death in 2022, accounted for 5.7% of deaths in the United States. The number of deaths from COVID-19 decreased 55.3% from 416,893 in 2021 to 186,552 in 2022.

In 2022, the age-adjusted death rate for COVID-19 decreased 57.3%, from 104.1 per 100,000 standard population in 2021 to 44.5 in 2022. The rate for males (56.7) was 1.6 times higher than the rate for females (35.4) (Tables B and 11). Among race and ethnicity groups, the rate was highest for the American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native) population (65.9), followed by Black non-Hispanic (subsequently, Black) (53.9), Native Hawaiian or Other Pacific Islander non-Hispanic (subsequently, Native Hawaiian or Other Pacific Islander) (48.9), Hispanic (47.2), White non-Hispanic (subsequently, White) (43.9), and Asian non-Hispanic (subsequently, Asian) (25.3) populations (Tables 1 and 11).

Other leading causes of death that showed significant decreases in 2022 from 2021 were stroke (3.9%), Chronic lower respiratory diseases (1.2%), Alzheimer disease (6.8%), diabetes (5.1%), Chronic liver disease and cirrhosis (4.8%), hypertension (3.7%), and Parkinson disease (3.1%).

The age-adjusted rate increased significantly in 2022 from 2021 for kidney disease (1.5%) and Influenza and pneumonia (7.6%).

The age-adjusted death rates for suicide and Septicemia in 2022 were not significantly different from the rates in 2021.

The relative risk of death in one population group compared with another can be expressed as a ratio. Ratios based on age-adjusted death rates show that males have higher rates than females for 14 of the 15 leading causes of death (Table B), with rates for males being at least twice as great as those for females for 3 of these leading causes. The largest ratio was for suicide (3.9). Other high ratios were observed for unintentional injuries and Parkinson disease (2.3 each); Chronic liver disease and cirrhosis (1.8); heart disease, COVID-19, and diabetes (1.6 each); kidney disease and Influenza and pneumonia (1.4 each); cancer and Septicemia (1.3 each); hypertension (1.2); and stroke and Chronic lower respiratory diseases (1.1 each). Age-adjusted rates were lower for males than for females for one leading cause, Alzheimer disease (0.7).

Age-adjusted death rates for the American Indian and Alaska Native population were higher than for the White population for 8 of the 15 leading causes of death (Tables B and 6). The largest ratio was for Chronic liver disease and cirrhosis (4.4). Other causes for which the ratio was high include diabetes (2.2); unintentional injuries (1.9); COVID-19 and suicide (1.5 each); kidney disease and Influenza and pneumonia (1.4 each); and Septicemia (1.3). Age-adjusted rates for the American Indian and Alaska Native population were lower than for the White population for 6 of the 15 leading causes of death. The smallest American Indian and Alaska Native-to-White ratio was for Parkinson disease (0.4); that is, the risk of dying from Parkinson disease was more than two times greater for the White population than for the American Indian and Alaska Native population. Other causes with a low American Indian and Alaska Native-to-White ratio were Alzheimer disease (0.5); Chronic lower respiratory diseases (0.7); cancer and stroke (0.8 each); and heart disease (0.9).

Age-adjusted death rates for the Black population were higher than for the White population for 10 of the 15 leading causes of death (Tables B and 6). The largest ratio was for kidney disease (2.2). Other causes for which the ratio was high include diabetes and hypertension (2.0 each); Septicemia (1.7); stroke (1.5); heart disease (1.3); unintentional injuries and COVID-19 (1.2 each); and cancer and Influenza and pneumonia (1.1 each). For five of the leading causes, age-adjusted rates were lower for the Black population than for the White population. The smallest Black-to-White ratios were for suicide and Parkinson disease (0.5 each). Other causes with low Black-to-White ratios were Chronic liver disease and cirrhosis (0.6); Chronic lower respiratory diseases (0.7); and Alzheimer disease (0.9).

Age-adjusted death rates for the White population were higher than for the Asian population for each of the 15 leading causes of death (Tables B and 6). The highest ratios were for Chronic lower respiratory diseases (4.7); followed by unintentional injuries and Chronic liver disease and cirrhosis (3.6 each); suicide (2.6); Septicemia (2.2); heart disease (2.1); Alzheimer disease (1.9); Parkinson disease (1.8); cancer and COVID-19 (1.7 each); Influenza and pneumonia (1.4); stroke and kidney disease (1.3 each); diabetes (1.2); and hypertension (1.1)

Age-adjusted death rates for the White population were higher than Native Hawaiian or Other Pacific Islander population for 7 of the 15 leading causes of death (Tables B and 6). The highest ratios were for Chronic lower respiratory disease and chronic liver disease and cirrhosis (2.0 each); followed by Alzheimer disease (1.5); unintentional injuries (1.4); suicide (1.2); and cancer and Influenza and pneumonia (1.1 each). Age-adjusted death rates for the White population were lower than for the Native Hawaiian or Other Pacific Islander population for 6 of the 15 leading causes of death. The smallest ratio was for diabetes (0.4); followed by kidney disease (0.6); stroke (0.7); hypertension (0.8); and COVID-19 and Septicemia (0.9 each).

Age-adjusted death rates for the White population were higher than for the Hispanic population for 10 of the 15 leading causes of death (Tables B and 6). The largest ratio was for Chronic lower respiratory diseases (2.8). Other causes with high ratios include suicide (2.2); Parkinson disease (1.6); heart disease (1.5); cancer and unintentional injuries (1.4 each); Septicemia (1.3); Influenza and pneumonia (1.2); and stroke and Alzheimer disease (1.1 each). Age-adjusted rates were lower for the White population than for the Hispanic population for 3 of the 15 leading causes. The smallest White-to-Hispanic ratio was for diabetes (0.8), followed by COVID-19 and Chronic liver disease and cirrhosis (0.9 each).

Assault (homicide), the 16th leading cause of death in 2022, dropped from among the 15 leading causes of death in 2010. In 2022, the age-adjusted rate for homicide decreased 6.1%, from 8.2 in 2021 to 7.7 per 100,000 standard population in 2022 (Table 11). Homicide remains a major issue for some age groups. Homicide was among the 15 leading causes of death in 2022 for age groups 1–4 (3rd), 5–14 (3rd), 15–24 (2nd), 25–34 (3rd), 35–44 (6th), 45–54 (10th), and 55–64 (14th) (14) (For leading causes of infant death, see “Infant mortality”).

Although Human immunodeficiency virus (HIV) disease has not been among the 15 leading causes of death since 1997 (20), it is still considered a major public health problem for some age groups. The age-adjusted death rate (1.3 deaths per 100,000 U.S. standard population) for HIV disease remained unchanged statistically in 2022 from 2021 (Table 11). Historically, for all ages combined, HIV disease mortality reached its highest level in 1995 after a period of increase from 1987 through 1994. Subsequently, the rate for this disease decreased an average of 33.0% per year from 1995 through 1998, and 6.1% per year from 1999 through 2021 (9,13). In 2022, HIV disease was among the 15 leading causes of death for age groups 25–34 (13th), 35–44 (13th), and 45–54 (15th). The influence of HIV disease for younger age groups and by race and ethnicity shows among the 25–34 age group, where its rank is 9th for males, 7th for Black males, 11th for Black females, and 10th for Hispanic males.

Enterocolitis due to Clostridium difficile (C. difficile)—A predominantly antibiotic-associated inflammation of the intestines caused by C. difficile, a gram-positive, anaerobic, spore-forming bacillus—is often acquired in hospitals or other health care facilities with long-term patients or residents (21,22). The number of deaths from C. difficile climbed from 793 deaths in 1999 to a high of 8,085 deaths in 2011 (14). From 2011 to 2021, the number of deaths from this cause trended downward. In 2022, the number of deaths from C. difficile was 4,231 (126 more deaths than in 2021). The age-adjusted death rate in 2022 was unchanged from 2021, 1.0 deaths per 100,000 standard population. About 85.4% of deaths from C. difficile occurred among people age 65 and older (Table 7).

Leading causes of death in 2022 for the total population and for specific subpopulations are detailed further in a companion National Vital Statistics Report on leading causes by age, Hispanic origin and race, and sex (2).

### Other selected causes

#### Dementia-related mortality

In 2022, 292,881 people died of dementia-related causes in the United States (Tables 7, 9, and 22). Deaths from dementia-related causes were presented for the first time in this report series in 2018 to provide a more comprehensive estimate of the burden of mortality from Alzheimer disease and other dementias in the United States.

Dementia-related causes include conditions with similar physical signs and symptoms that, collectively, are considered to be a good indicator of dementia mortality (23). Dementia is characterized by memory impairment and cognitive decline (24–26). Causes of death attributable to dementia-related mortality include ICD–10 codes F01, Vascular dementia; F03, Unspecified dementia; G30, Alzheimer disease; and G31, Other degenerative diseases of nervous system, not elsewhere classified. Alzheimer disease, the sixth leading cause of death, is the most common cause of dementia, but other dementias, including Lewy body dementia, frontotemporal degeneration, vascular dementia, and mixed dementias, are often indistinguishable from Alzheimer disease in their symptoms and outcomes and may coexist with Alzheimer disease (22–24).

Certification and coding rule changes can impact data analysis of component causes of dementia. In 2022, Alzheimer disease accounted for 41.0% of all dementia deaths; Unspecified dementia for 31.9%; Other degenerative diseases of nervous system, not elsewhere classified for 19.9%; and Vascular dementia for 7.1%. For detailed information, see CDC WONDER (14). Changes in the percentage of deaths assigned to individual causes comprising dementia may be the result of many factors (25). Combining the types of dementia provides a more comprehensive and stable measure of dementia mortality.

The age-adjusted death rate for dementia-related causes decreased 2.8% in 2022 from 2021 for the total population (from 72.4 to 70.4). The rate for females decreased 4.2% (80.2 to 76.8). The rate for males was unchanged (59.7) (Tables 11 and 22).

Among race–ethnicity groups—Age-adjusted rates for American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native) females decreased 11.8% (51.6 to 45.5). Rates for the total and female Black non-Hispanic (subsequently, Black) populations decreased 5.6% (71.8 to 67.8) and 7.9% (75.9 to 69.9), respectively. Rates for the total and female White non-Hispanic (subsequently, White) population decreased 2.8% (77.4 to 75.2) and 4.3% (86.3 to 82.6), respectively. Changes in age-adjusted death rates for dementia-related causes were not statistically significant for the other race–ethnicity–sex categories.

#### Drug-induced mortality

In 2022, a total of 112,109 people died of drug-induced causes in the United States (Tables 7, 9, and 23). The category of drug-induced causes includes deaths from drug overdose as well as from other medical conditions caused by use of legal or illegal drugs. In 2022, drug-overdose deaths accounted for 96.3% of all drug-induced deaths (Tables 7 and 9). The drug-induced category excludes deaths indirectly related to drug use, as well as newborn deaths due to the mother’s drug use. (For a list of all drug-induced causes including those specifically classified as drug-overdose causes, see Technical Notes.)

The age-adjusted death rate for drug-induced causes did not change significantly for the total, male, and female populations from 2021 to 2022 (Tables 6, 11, and 23). For males in 2022, the age-adjusted death rate for drug-induced causes was 2.3 times the rate for females.

Among race–ethnicity groups—Age-adjusted rates increased from 2021 and 2022 by 15.1% for the American Indian and Alaska Native population (20.3% for American Indian and Alaska Native males), 12.2% for the Asian population (14.5% for Asian males), 7.4% for the Black population (8.5% for Black males), and 6.8% for the Hispanic population (8.4% for Hispanic males). Rates for the White population decreased 3.4% (3.9% for White males and 2.8% for White females) (Tables 11 and 23). Changes in age-adjusted rates from 2021 to 2022 were not significant for other race–ethnicity–sex categories.

#### Alcohol-induced mortality

In 2022, a total of 51,191 people died of alcohol-induced causes in the United States (Tables 7, 9, and 24). This category includes deaths from dependent and nondependent use of alcohol, and deaths from accidental poisoning by alcohol. It excludes unintentional injuries, homicides, and other causes indirectly related to alcohol use, and deaths due to fetal alcohol syndrome. For a list of alcohol-induced causes, see Technical Notes.

The age-adjusted death rate for alcohol-induced causes decreased 6.3% for the total population, from 14.4 in 2021 to 13.5 in 2022 (Tables 6, 11, and 24). For males in 2022, the age-adjusted death rate for alcohol-induced causes was 2.5 times the rate for females. The rate decreased 6.7% for males and 6.0% for females from 2021 to 2022 (Tables 11 and 24).

Among race–ethnicity groups—Age-adjusted rates decreased in 2022 from 2021 by 14.5% for the American Indian and Alaska Native population (15.2% for American Indian and Alaska Native males and 13.5% for American Indian and Alaska Native females), 13.4% for the Black population (12.7% for Black males and 14.9% for Black females), 4.0% for Hispanic males, and 5.1% for the White population (6.0% for White males and 4.2% for White females) (Tables 11 and 24). The age-adjusted rate for alcohol-induced death did not change significantly in 2022 from 2021 for other race–ethnicity–sex categories.

#### Firearm-related mortality

In 2022, 48,204 people died from firearm-related injuries in the United States (Tables 7, 9, and 25). The age-adjusted death rate for firearm-related injuries for the total and male populations decreased significantly from 2021 to 2022 by 2.7% and 2.8%, respectively (Tables 6, 11, and 25). For males in 2022, the age-adjusted death rate for firearm-related injuries was 6.0 times the rate for females.

Among race–ethnicity groups—The age-adjusted death rate increased in 2022 from 2021 by 16.2% for the American Indian and Alaska Native population (17.4% for American Indian and Alaska Native males). The rates decreased 7.8% for the total, male, and female Black populations (Tables 11 and 25). The age-adjusted death rates for firearm-related injuries did not change significantly in 2022 from 2021 for other race–ethnicity–sex categories.

### Effect on life expectancy of changes in mortality by age and cause of death

Changes in mortality by age and cause of death can have a major effect on life expectancy. In other words, year-to-year changes in life expectancy may be influenced by changes in age-specific rates for certain causes, particularly for younger age groups. Life expectancy at birth for the total population increased by 1.1 years (from 76.4 years in 2021 to 77.5 years in 2022) primarily because of decreases in mortality from COVID-19, heart disease, cancer, unintentional injuries, and homicide (Table 5). The increase in life expectancy for the total population was slightly offset by increases in mortality from Influenza and pneumonia, perinatal conditions, kidney disease, nutritional deficiencies, and congenital malformations. Life expectancy at birth for males increased by 1.3 years (from 73.5 years in 2021 to 74.8 years in 2022) due to decreases in mortality from COVID-19, heart disease, cancer, homicide, and unintentional injuries. The increase in life expectancy was offset somewhat by increases in mortality from perinatal conditions, Influenza and pneumonia, kidney disease, nutritional deficiencies, and congenital malformations. For the female population, life expectancy increased by 0.9 year (from 79.3 years in 2021 to 80.2 years in 2022) due to decreases in mortality from COVID-19, unintentional injuries, heart disease, diabetes, and cancer. This increase was offset by increases in mortality from Influenza and pneumonia, Chronic lower respiratory diseases, nutritional deficiencies, kidney disease, and perinatal conditions. (For a discussion of the major causes contributing to the change in life expectancy, see Technical Notes.)

Life expectancy for the American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native) population increased by 2.2 years to 67.8 years. This increase was primarily due to decreases in mortality from COVID-19, Chronic liver disease and cirrhosis, cancer, suicide, and diabetes. The increase in life expectancy was offset by increases in mortality due to unintentional injuries, homicide, perinatal conditions, Influenza and pneumonia, and congenital malformations. Life expectancy for the American Indian and Alaska Native male population increased 2.3 years to 64.5 years. This increase, primarily due to decreases in mortality from COVID-19, Chronic liver disease and cirrhosis, heart disease, cancer, and suicide, was offset somewhat by increases in mortality from unintentional injuries, perinatal conditions, homicide, legal intervention, and congenital malformation. Life expectancy for the American Indian and Alaska Native female population increased 2.1 years from 69.2 years in 2021 to 71.3 years in 2022. This increase in life expectancy, primarily due to decreases in mortality from COVID-19, Chronic liver disease and cirrhosis, Chronic lower respiratory diseases, diabetes, and Alzheimer disease, was offset somewhat by increases in mortality from Influenza and pneumonia, homicide, heart disease, cancer, and benign neoplasms.

Life expectancy for the Black non-Hispanic (subsequently, Black) population in 2022 increased 1.6 years to 72.8 years. This increase, due to decreases in mortality from COVID-19, heart disease, homicide, diabetes, and Chronic liver disease and cirrhosis, was offset by increases in mortality from perinatal conditions, kidney disease, congenital malformations, nutritional deficiencies, and legal intervention. Life expectancy for the Black male population in 2022 increased 1.5 years to 69.1 years. This increase, due to decreases in mortality from COVID-19, homicide, heart disease, diabetes, and cancer, was offset by increases in mortality from perinatal conditions, congenital malformations, kidney disease, anemias, and legal intervention. Life expectancy for the Black female population increased 1.5 years in 2022 to 76.5 years due to decreases in mortality from COVID-19, heart disease, diabetes, homicide, and Chronic liver disease and cirrhosis. This increase was offset somewhat by increases in mortality from perinatal conditions, kidney disease, Influenza and pneumonia, aortic aneurysm, and unintentional injuries.

Life expectancy for the Asian non-Hispanic (subsequently, Asian) population increased 0.9 year to 84.4 years. The increase, primarily due to decreases in mortality from COVID-19, stroke, cancer, hypertension, and diabetes, was offset by increases in mortality due to kidney disease, heart disease, congenital malformations, unintentional injuries, and nutritional deficiencies. Life expectancy for the Asian male population increased 1.1 years in 2022 to 82.3 years due to decreases in mortality from COVID-19, stroke, perinatal conditions, diabetes, and cancer. This increase was offset somewhat by increases in mortality from unintentional injuries, kidney disease, congenital malformations, septicemia, and meningitis. Life expectancy for the Asian female population increased by 0.7 year in 2022 to 86.3 years due to decreases in mortality from COVID-19, cancer, stroke, perinatal conditions, and unintentional injuries. This increase was offset somewhat by increases in mortality from Influenza and pneumonia, kidney disease, nutritional deficiencies, pneumonitis, and C. difficile.

Life expectancy for the White non-Hispanic (subsequently, White) population increased 0.8 year in 2022 to 77.5 years (Table 4). This increase, due to decreases in mortality from COVID-19, unintentional injuries, heart disease, cancer, and Chronic liver disease and cirrhosis, was offset to some extent by increases in mortality from Influenza and pneumonia, perinatal conditions, nutritional deficiencies, kidney disease, and Chronic lower respiratory diseases. Life expectancy for the White male population increased 1.1 years in 2022 to 75.1 years due to decreases in mortality from COVID-19, unintentional injuries, heart disease, cancer, and suicide. This increase was offset somewhat by increases in mortality from perinatal conditions, Influenza and pneumonia, kidney disease, nutritional deficiencies, and Parkinson disease. Life expectancy for White females increased 0.6 year in 2022 to 80.1 years. This increase, due to decreases in mortality from COVID-19, unintentional injuries, diabetes, cancer, and medical complications, was offset somewhat by increases in mortality from Influenza and pneumonia, Chronic lower respiratory diseases, nutritional deficiencies, perinatal conditions, and kidney disease.

Life expectancy for the Hispanic population increased by 2.2 years to 80.0 years. This increase, due to decreases in mortality from COVID-19, heart disease, diabetes, cancer, and medical complications, was offset by increases in mortality from unintentional injuries, Influenza and pneumonia, congenital malformations, perinatal conditions, and nutritional deficiencies. Life expectancy for the Hispanic male population in 2022 increased 2.4 years to 77.0 years due to decreases in mortality from COVID-19, heart disease, Chronic liver disease, diabetes, and homicide. This increase was offset somewhat by increases in mortality from unintentional injuries, perinatal conditions, congenital malformations, Influenza and pneumonia, and legal intervention. Life expectancy for the Hispanic female population increased by 1.7 years in 2022 to 82.8 years due to decreases in mortality from COVID-19, heart disease, cancer, diabetes, and stroke. This increase was offset somewhat by increases in mortality from Influenza and pneumonia, congenital malformations, chronic liver disease, kidney disease, and homicide.

The difference in life expectancy between the male and female populations decreased 0.4 year in 2022 to 5.4 years (Table 4). The narrowing in the male–female life expectancy gap was due primarily to greater decreases in mortality for the male population from COVID-19, heart disease, homicide, cancer, and Chronic lower respiratory diseases (data not shown).

### Injury mortality by mechanism and intent

In 2022, a total of 307,785 deaths were classified as injury-related (Table 12). Injury data are presented using the external cause-of-injury mortality matrix for ICD–10, as jointly conceived by the International Collaborative Effort on Injury Statistics and the Injury Control and Emergency Health Services section of the American Public Health Association (27,28). The ICD codes for injuries have two essential dimensions: the mechanism of the injury and its manner or intent. The mechanism involves the circumstances of the injury (such as fall, motor-vehicle traffic, or poisoning). The manner or intent involves whether the injury was purposefully inflicted (where it can be determined) and, when intentional, whether the injury was self-inflicted (suicide) or inflicted upon another person (assault). In other report tables showing cause of death, the focus is on manner or intent, with subcategories showing selected mechanisms. The matrix has two distinct advantages for the analysis of injury mortality data: It contains a comprehensive list of mechanisms, and data can be displayed by mechanism with subcategories of intent, or vice versa. Four major mechanisms of injury in 2022—poisoning, firearm, fall, and motor-vehicle traffic—accounted for 82.3% of all injury deaths.

A total of 112,728 deaths occurred as the result of poisonings in 2022, accounting for 36.6% of all injury deaths (Table 12). The age-adjusted death rate for poisoning did not change significantly from 2021 to 2022. Most poisoning deaths were either unintentional (91.3%) or suicides (5.5%). However, 3.0% of poisoning deaths were of undetermined intent. The age-adjusted death rate for unintentional poisoning was unchanged statistically from 2021 to 2022.

Firearm injuries resulted in 48,204 deaths in 2022 (Table 12), accounting for 15.7% of all injury deaths. The age-adjusted death rate for firearm injuries (all intents) in 2022 decreased 2.7% from 2021. The two major component causes of firearm injury deaths in 2022 were suicide (56.1%) and homicide (40.8%). The age-adjusted death rate for firearm suicide did not change significantly from 2021 to 2022. The age-adjusted rate for firearm homicide decreased 7.5%, from 6.7 in 2021 to 6.2 in 2022.

A total of 47,984 people died as the result of falls in 2022, accounting for 15.6% of all injury deaths (Table 12). The age-adjusted death rate for falls in 2022 decreased 1.7%, from 11.8 in 2021 to 11.6 in 2022. The overwhelming majority of fall-related deaths (97.2%) were unintentional.

Motor vehicle traffic-related injuries in 2022 resulted in 44,534 deaths, accounting for 14.5% of all injury deaths (Table 12). The age-adjusted death rate for these injuries decreased 3.0%, from 13.3 in 2021 to 12.9 in 2022.

### Marital status

For those age 15 and older, the number of deaths in 2022 among people who were married was 1,170,668; widowed, 998,284; divorced, 576,726; and never married, 474,143 (Table 13); see Technical Notes. Those who were widowed had the highest age-adjusted death rate (1,880.3 per 100,000 U.S. standard population), followed by never-married people (1,623.5), divorced people (1,514.4), and married people (790.4). Never-married people had an age-adjusted death rate 45.4% higher than those ever-married (more than 2 times the rate of currently married people and 7.2% higher than divorced people). Widowed people had a rate more than twice that of married people, 24.2% higher than divorced people, and 15.8% higher than never-married people. Divorced people had a rate 1.9 times the rate of those who were married at the time of death.

For all age groups 15 and older, age-specific death rates for married people were much lower than those for never-married people. For those ages 15–24, divorced people had the highest death rate, whereas for those ages 25–34, 35-44, and 75 and older, widowed people had the highest death rate. Never-married people had the highest death rate among those ages 45–54, 55–64, and 65–74 (Table 13).

For each marital status group in 2022, males had higher age-adjusted death rates than females, ranging from 55.9% greater for those never married and widowed to 69.5% higher for those divorced at the time of death (Table 13).

### Educational attainment

Age-specific and age-adjusted death rates are shown by educational attainment for age groups in the range of 25–64 years (Table 14). In 2022, a total of 358,700 decedents ages 25–64 had received a high school diploma or equivalent, compared with 271,100 who had completed some college or collegiate degree and 137,271 who had achieved less than a high school diploma or equivalent. In 2022, age-adjusted death rates for those with less than a high school diploma or GED (695.7 per 100,000 U.S. standard population) and for those with a high school diploma or GED (724.4) were more than 3 times the rate for those with some college or collegiate degree (220.3).

### Injury at work

Deaths, crude death rates, and age-adjusted death rates for injury at work are shown for those age 15 and older (Tables 15 and 16). Age-adjusted death rates for injury at work were computed using age-specific death rates and the 2000 U.S. standard population for those age 15 and older; see “Computing rates” in Technical Notes. Information on deaths attributed to injuries at work is derived from a separate item on the death certificate that asks the medical certifier whether the death resulted from an injury sustained at work. This item is on the death certificate of all states.

### State of residence

Mortality patterns varied considerably by state (Tables 17 and 20). The state with the highest age-adjusted death rate in 2022 was West Virginia (1,115.6 deaths per 100,000 U.S. standard population), with a rate 39.7% above the national rate (798.8). The state with the lowest age-adjusted death rate was Hawaii (615.9), with a rate 22.9% below the national rate. The age-adjusted death rate for West Virginia was 81.1% higher than the rate for Hawaii.

Variations in mortality by state were associated with differences in socioeconomic status, racial and ethnic composition, as well as with differences in risk of specific causes of death (29).

### Infant mortality

In 2022, a total of 20,553 deaths occurred in children younger than age 1 year (Tables C, D, 19, and 20). This number represents 633 more infant deaths in 2022 than in 2021. The ratio of male-to-female IMRs was 1.2, the same as in 2021. IMR was 5.60 infant deaths per 1,000 live births, the neonatal mortality rate (deaths of infants ages 0–27 days per 1,000 live births) was 3.58, and the postneonatal mortality rate (deaths of infants ages 28 days–11 months per 1,000 live births) was 2.03 in 2022 (Figure 5 and Tables C and 18; see Technical Notes for information on alternative data sources).

Figure 5 Infant, neonatal, and postneonatal mortality rates: United States, 1960–2022

NOTE: Rates are infant (younger than 1 year), neonatal (younger than 28 days), and postneonatal (28 days–11 months) deaths per 1,000 live births in specified group.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 5 is a line graph showing infant, neonatal, and postneonatal mortality rates in the United States from 1960 through 2022.

Table C Number of infant, neonatal, and postneonatal deaths and mortality rate, by sex: United States, 2021–2022

[Rates are infant (younger than 1 year), neonatal (younger than 28 days), and postneonatal (28 days–11 months) deaths per 1,000 live births in specified group]

Age and sex | 2022 | | 2021 | | Percent change^1^ from 2021 to 2022
Age and sex | Number | Rate | Number | Rate | Percent change^1^ from 2021 to 2022
Infant
Total | 20,553 | 5.60 | 19,920 | 5.44 | 2.9
Male | 11,371 | 6.07 | 10,909 | 5.82 | 4.3
Female | 9,182 | 5.12 | 9,011 | 5.03 | 1.8
Neonatal
Total | 13,125 | 3.58 | 12,768 | 3.48 | 2.9
Male | 7,130 | 3.80 | 6,899 | 3.68 | 3.3
Female | 5,995 | 3.34 | 5,869 | 3.28 | 1.8
Postneonatal
Total | 7,428 | 2.03 | 7,152 | 1.95 | 4.1
Male | 4,241 | 2.26 | 4,010 | 2.14 | 5.6
Female | 3,187 | 1.78 | 3,142 | 1.75 | 1.7

^1^Based on a comparison of 2022 and 2021 mortality rates.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table D Number of infant deaths, percentage of total infant deaths, and infant mortality rate for 2022, and percent change in infant mortality rates from 2021 to 2022 for the 10 leading causes of infant death in 2022: United States

[Rates are infant deaths per 100,000 live births]

Rank^1^ | Cause of death (based on International Classification of Diseases, 10h Revision) | Number | Percent of total deaths^2^ | Rate | Percent change^3^ from 2021 to 2022
… | All causes | 20,553 | 100.0 | 560.4 | 3.1
1 | Congenital malformations, deformations and chromosomal abnormalities(Q00–Q99) | 3,970 | 19.3 | 108.2 | 0.0
2 | Disorders related to short gestation and low birth weight, not elsewhere classified (P07) | 2,884 | 14.0 | 78.6 | -2.2
3 | Sudden infant death syndrome(R95) | 1,529 | 7.4 | 41.7 | 4.8
4 | Accidents (unintentional injuries)(V01–X59) | 1,354 | 6.6 | 36.9 | 3.7
5 | Newborn affected by maternal complications of pregnancy(P01) | 1,215 | 5.9 | 33.1 | 8.9
6 | Newborn affected by complications of placenta, cord and membranes(P02) | 649 | 3.2 | 17.7 | -3.3
7 | Bacterial sepsis of newborn(P36) | 636 | 3.1 | 17.3 | 13.8
8 | Respiratory distress of newborn(P22) | 455 | 2.2 | 12.4 | 9.7
9 | Intrauterine hypoxia and birth asphyxia(P20–P21) | 362 | 1.8 | 9.9 | 1.0
10 | Diseases of the circulatory system(I00–I99) | 356 | 1.7 | 9.7 | -11.8
… | All other causes(residual) | 7,143 | 34.8 | 194.8 | …

… Category not applicable.

^1^Based on number of deaths; see Technical Notes in this report.

^2^Percentages may not add to 100 due to rounding.

^3^Based on a comparison of the 2022 infant mortality rate with the 2021 infant mortality rate.

NOTE: Due to rounding, percent changes based on rates per 100,000 live births may differ from those computed using rates per 1,000 live births.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

The infant, neonatal, and postneonatal mortality rates increased significantly by 2.9%, 2.9%, and 4.1% from 2021 to 2022, respectively.

The 10 leading causes of infant death in 2022 accounted for 65.2% of all infant deaths in the United States (Table D). By rank, the 10 leading causes were:

1. Congenital malformations, deformations and chromosomal abnormalities (congenital malformations)
2. Disorders related to short gestation and low birth weight, not elsewhere classified (low birth weight)
3. Sudden infant death syndrome (SIDS)
4. Accidents (unintentional injuries)
5. Newborn affected by maternal complications of pregnancy (maternal complications)
6. Newborn affected by complications of placenta, cord and membranes (cord and placental complications)
7. Bacterial sepsis of newborn
8. Respiratory distress of newborn
9. Intrauterine hypoxia and birth asphyxia
10. Diseases of the circulatory system

The 10 leading causes of infant death remained unchanged in 2022 from 2021, although two causes changed ranks (30). Intrauterine hypoxia and birth asphyxia, the 10th leading cause of infant death in 2021, became the 9th leading cause in 2022, while Diseases of the circulatory system, the 9th leading cause in 2021, became the 10th leading cause in 2022. Among the 10 leading causes, IMR increased 8.9% from 2021 for maternal complications and 13.8% for bacteria sepsis of newborn. Changes in rates among the other leading causes of infant death were not statistically significant (Table D).

IMRs by race for non-Hispanic origin that are based on the mortality file may be somewhat understated and are better measured using data from the linked file of live births and infant deaths (31); see Technical Notes. Infant mortality data presented in this report use the general mortality file, not the linked file of live births and infant deaths. IMRs for the Hispanic population are not adjusted for misclassification; see Technical Notes. Because these rates are not adjusted, misclassification of Hispanic origin should be considered when interpreting rate disparities between Hispanic and non-Hispanic populations (16).

In 2022, the IMR for White non-Hispanic infants was 4.39 per 1,000 live births, an increase of 4.5% from 4.20 in 2021. In 2022, the IMR was 5.08 for Hispanic infants, 8.16 for American Indian and Alaska Native non-Hispanic infants, 2.85 for Asian non-Hispanic infants, 11.34 for Black non-Hispanic infants, and 8.79 for Native Hawaiian or Other Pacific Islander non-Hispanic infants (Table 18). The changes in IMRs in 2022 from 2021 for these groups were not statistically significant.

### Maternal mortality

In 2022, a total of 817 women died of maternal causes in the United States—388 fewer deaths than in 2021 (Table 21) (30). The overall maternal mortality rate decreased 32.2%, from 32.9 deaths per 100,000 live births in 2021 to 22.3 in 2022. COVID-19 was listed on the death certificate as a contributing cause of death for 10.8% of maternal deaths in 2022 (14). The maternal mortality rate in 2022 was highest for Black non-Hispanic (subsequently, Black) women (49.5), followed by White non-Hispanic (subsequently, White) (19.0), Hispanic (16.9), and Asian non-Hispanic (subsequently, Asian) (13.2) women. The maternal mortality rate decreased 39.6% for Hispanic women (from 28.0 in 2021 to 16.9 in 2022), 29.2% for Black women (from 69.9 in 2021 to 49.5 in 2022) and 28.6% for White women (from 26.6 to 19.0). The change in maternal mortality rates for Asian women was not significant. In 2022, the maternal mortality rates for American Indian and Alaska Native women and Native Hawaiian or Other Pacific Islander women did not meet National Center for Health Statistics standards of reliability because the numbers of deaths are too low.

Maternal deaths and death rates shown in this report are based on the new method for coding maternal deaths that was adopted by the National Center for Health Statistics starting with the 2018 data year (30) (Technical Notes). This method restricts application of the pregnancy checkbox to decedents ages 10–44 for coding cause of death to a maternal cause when the certificate has no mention of a maternal-related condition but has a positive checkbox entry (30). For women age 45 and older, the checkbox is used in coding cause of death only if a positive checkbox entry is accompanied by a mention of a maternal-related condition as a cause of death. Maternal deaths include deaths of women while pregnant or within 42 days of being pregnant, from any cause related to or aggravated by the pregnancy but exclude deaths from external causes (that is, accidents, homicides, and suicides); for more information, see “Maternal Mortality in the United States: Changes in Coding, Publication, and Data Release, 2018” (32) and Technical Notes.

## References

1 Hoyert DL, Singh GK, Rosenberg HM. Sources of data on socio-economic differential mortality in the United States. Jour Off Stat 1995;11(3):233–60.
2 Curtin SC, Tejada-Vera B, Bastian BA. Deaths: Leading causes for 2022. Natl Vital Stat Rep. 2024 Dec;73(10):1–117. DOI: 10.15620/cdc/164020.
3 Arias E, Xu JQ, Kochanek KD. United States life tables, 2022. Natl Vital Stat Rep. 2025 Apr;74(2):1–64. DOI: 10.15620/cdc/174575.
4 World Health Organization. International statistical classification of diseases and related health problems, 10th revision. 2008 ed. 2009.
5 National Vital Statistics System. Volume 1. ICD–10, International statistical classification of diseases and related health problems. Tabular list. (Modified by NCHS for use in the classification and analysis of medical mortality data in the United States) NCHS Instruction Manual; part 2e, vol 1. Published annually. Available from: https://www.cdc.gov/nchs/nvss/instruction_manuals.htm.
6 National Vital Statistics System. Volume 1. ICD–10, International statistical classification of diseases and related health problems. Alphabetical index. (Modified by NCHS for use in the classification and analysis of medical mortality data in the United States) NCHS Instruction Manual; part 2e, vol 3. Published annually. Available from: https://www.cdc.gov/nchs/nvss/instruction_manuals.htm.
7 National Center for Health Statistics. 2003 revision of the U.S. Standard Certificate of Death. 2003. Available from: https://www.cdc.gov/nchs/data/dvs/DEATH11-03final-acc.pdf.
8 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist 62FR58782. 1997. Available from: https://www.govinfo.gov/content/pkg/FR-1997-10-30/pdf/97-28653.pdf.
9 Murphy SL, Xu JQ, Kochanek KD, Arias E, Tejada-Vera B. Deaths: Final Data for 2018. Natl Vital Stat Rep. 2021 Jan;69(13):1–83. PMID: 33541516. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr69/nvsr69-13-508.pdf.
10 Office of Management and Budget. Race and ethnic standards for federal statistics and administrative reporting. Statistical Policy Directive no 15. 1977. Available from: https://wonder.cdc.gov/wonder/help/populations/bridged-race/directive15.html.
11 Heron M. Comparability of Race-specific Mortality Data Based on 1977 Versus 1997 Reporting Standards. Natl Vital Stat Rep. 2021 Apr;70(3):1–31. PMID: 34029180. DOI: 10.15620/cdc:103476.
12 National Center for Health Statistics. Vital statistics online data portal: Mortality multiple cause files. National Center for Health Statistics. Published annually. Available from: https://www.cdc.gov/nchs/data_access/VitalStatsOnline.htm.
13 National Center for Health Statistics. National Vital Statistics System: Data release policy for vital statistics micro-data files. Available from: https://www.cdc.gov/nchs/nvss/dvs_data_release.htm.
14 Centers for Disease Control and Prevention. CDC WONDER. Available from: https://wonder.cdc.gov/.
15 Tolson GC, Barnes JM, Gay GA, Kowaleski JL. The 1989 revision of the U.S. Standard Certificates and Reports. Vital Health Stat 4. 1991 Jun;(28):1–34. PMID: 1713727. Available from: https://www.cdc.gov/nchs/data/series/sr_04/sr04_028.pdf.
16 Arias E, Heron M, Hakes J. The validity of race and Hispanic-origin reporting on death certificates in the United States: An update. Vital Health Stat 2. 2016 Aug 1;(172):1–29. PMID: 28436642. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_172.pdf.
17 Centers for Disease Control and Prevention. CDC WONDER. Single-race population estimates, United States, 2020–2022. July 1st resident population by state, age, sex, single-race, and Hispanic origin. Data source: Vintage 2022 estimates released by U.S. Census Bureau on June 22, 2023. Available from: https://wonder.cdc.gov/single-race-population.html.
18 Arias E. United States life tables by Hispanic origin. National Center for Health Statistics. Vital Health Stat 2. 2010 Oct;(152):1–35. PMID: 21313788. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_152.pdf.
19 Arias E, Xu JQ. Arias E, Xu J. United States Life Tables, 2019. Natl Vital Stat Rep. 2022 Mar;70(19):1–59. PMID: 35319436. DOI: 10.15620/cdc:113096.
20 Hoyert DL, Kochanek KD, Murphy SL. Deaths: Final data for 1997. Natl Vital Stat Rep. 1999 Jun 30;47(19):1–104. PMID: 10410536. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr47/nvs47_19.pdf.
21 Sunenshine RH, McDonald LC. Clostridium difficile-associated disease: New challenges from an established pathogen. Cleve Clin J Med. 2006 Feb;73(2):187–97. PMID: 16478043. Available from: https://www.ccjm.org/content/73/2/187.long.16478043
22 Redelings MD, Sorvillo FJ, Mascola L. Increase in Clostridium difficile-related mortality rates, United States, 1999– 2004. Emerg Infect Dis. 2007 Sep;13(9):1417–9. PMID: 18252127. Available from: https://wwwnc.cdc.gov/eid/article/13/9/06-1116_article.
23 World Health Organization. Dementia. Available from: https://www.who.int/news-room/fact-sheets/detail/dementia.
24 National Institute on Aging. Alzheimer’s disease fact sheet. Available from: https://www.nia.nih.gov/alzheimers/publication/alzheimers-disease-fact-sheet.
25 U.S. Department of Health and Human Services. National plan to address Alzheimer’s disease: 2019 update. 2019. Available from: https://aspe.hhs.gov/system/files/pdf/262601/NatlPlan2019.pdf.
26 Kramarow EA, Tejada-Vera B. Dementia Mortality in the United States, 2000– 2017. Natl Vital Stat Rep. 2019 Mar;68(2):1–29. PMID: 31112120. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr68/nvsr68_02-508.pdf.
27 National Center for Health Statistics. Proceedings of the international collaborative effort on injury statistics. 1995 Mar;1:1–330. Available from: https://stacks.cdc.gov/view/cdc/11212/cdc_11212_DS1.pdf?download-document-submit=Download.
28 Fingerhut LA, Cox CS, Warner M, participants of the International Collaborative Effort on Injury Statistics. International comparative analysis of injury mortality: Findings from the ICE on Injury Statistics. Advance Data from Vital and Health Statistics; no 303. National Center for Health Statistics. 1998. Available from: https://www.cdc.gov/nchs/data/ad/ad303.pdf.
29 Pamuk ER, Makuc DM, Heck KE, Reuben C, Lochner K. Socioeconomic status and health chartbook. Health, United States, 1998. National Center for Health Statistics. 1998. Available from: https://www.cdc.gov/nchs/data/hus/hus98.pdf.
30 Murphy SL, Kochanek KD, Xu JQ, Arias E. Deaths: Final data for 2021. Natl Vital Stat Rep. 2024 Oct;73(8):1–139. DOI: 10.15620/cdc/158787.
31 National Center for Health Statistics. User guide to the 2022 period/2021 cohort linked birth/infant death public use file. 2024. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/period-cohort-linked/22PE21CO_linkedUG.pdf.
32 Hoyert DL, Miniño AM. Maternal Mortality in the United States: Changes in Coding, Publication, and Data Release, 2018. Natl Vital Stat Rep. 2020 Jan;69(2):1–18. PMID: 32510319. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr69/nvsr69-02-508.pdf.
33 World Health Organization. International statistical classification of diseases and related health problems, 10th revision. 1992.
34 National Center for Health Statistics. Comparability of cause-of-death between ICD revisions. 2015. Available from: https://www.cdc.gov/nchs/nvss/mortality/comparability_icd.htm.
35 National Center for Health Statistics. Updated comparability ratios (ICD–10 and ICD–9). 2004. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Datasets/Comparability/icd9_icd10/.
36 Anderson RN, Miniño AM, Hoyert DL, Rosenberg HM. Comparability of cause of death between ICD–9 and ICD–10: Preliminary estimates. Natl Vital Stat Rep. 2001 May 18;49(2):1–32. PMID: 11381674. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr49/nvsr49_02.pdf.
37 Faust MM, Dolman AB. Comparability of mortality statistics for the sixth and seventh revisions: United States, 1958. Vital Statistics—Special Reports 51(4):248–97. National Center for Health Statistics. 1965. Available from: https://www.cdc.gov/nchs/data/spec_rpt51_04.pdf.
38 Klebba AJ, Dolman AB. Comparability of mortality statistics for the seventh and eighth revisions of the International Classification of Diseases, United States. Vital Health Stat 2. 1975;(66):1–93. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_066.pdf.
39 Klebba AJ, Scott JH. Estimates of selected comparability ratios based on dual coding of 1976 death certificates by the eighth and ninth revisions of the International Classification of Diseases. Monthly Vital Statistics Report; vol 28 no 11. National Center for Health Statistics. 1980. Available from: https://www.cdc.gov/nchs/data/mvsr/supp/mv28_11s.pdf.
40 National Center for Health Statistics. Instruction manuals. Current manuals. Part 2a: Instructions for classifying the underlying cause-of-death. Published annually. Available from: https://www.cdc.gov/nchs/nvss/instruction_manuals.htm.
41 National Center for Health Statistics. Instruction manuals. Current manuals. Part 2b: Instructions for classifying the multiple causes of death. Published annually. Available from: https://www.cdc.gov/nchs/nvss/instruction_manuals.htm.
42 National Center for Health Statistics. Instruction manuals. Current manuals. Part 2c: ICD–10 ACME decision tables for classifying underlying causes of death. Published annually. Available from: https://www.cdc.gov/nchs/nvss/instruction_manuals.htm.
43 National Center for Health Statistics. Instruction manuals. Historic manuals—Prior to ICD–10. Part 2g: Data entry instructions for the mortality medical indexing, classification, and references system (MICAR), 1996–1997. Available from: https://www.cdc.gov/nchs/nvss/instruction_manuals.htm.
44 National Center for Health Statistics. Instruction manuals. Historic manuals—ICD–10. Part 2s: SuperMICAR data entry instructions. Available from: https://www.cdc.gov/nchs/nvss/instruction_manuals.htm.
45 National Center for Health Statistics. Multiple cause of death public use file Control Total Table 1. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/mortality/Multiple-Cause-of-Death-Public-Use-File-Control-Total-Table-2022.pdf.
46 Chamblee RF, Evans MC. TRANSAX: The NCHS system for producing multiple cause-of-death statistics, 1968–78. Vital Health Stat 1 1986;(20):1–83. 1986. Available from: https://www.cdc.gov/nchs/data/series/sr_01/sr01_020acc.pdf.
47 Israel RA, Rosenberg HM, Curtin LR. Analytical potential for multiple cause-of-death data. Am J Epidemiol 1986 Aug;124(2):161–79. PMID: 3524199. Available from: https://aje.oxfordjournals.org/content/124/2/161.full.pdf.3524199
48 National Center for Health Statistics. Instruction manual, part 9: ICD–10 cause-of-death lists for tabulating mortality statistics (updated October 2020 to include WHO updates to ICD–10 for data year 2020). 2020. Available from: https://www.cdc.gov/nchs/data/dvs/Part9InstructionManual2020-508.pdf.
49 Hoyert DL, Arias E, Smith BL, Murphy SL, Kochanek KD. Deaths: Final data for 1999. Natl Vital Stat Rep. 2001 Sep 21;49(8):1–113. PMID: 11591077. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr49/nvsr49_08.pdf.
50 National Center for Health Statistics. Excess deaths associated with COVID-19. 2023 Available from: https://www.cdc.gov/nchs/nvss/vsrr/covid19/excess_deaths.htm.
51 Ahmad FB, Cisewski JA, Xu J, Anderson RN. Provisional mortality data—United States, 2022. MMWR Morb Mortal Wkly Rep 2023 May 5;72(18):488–92. DOI: 10.15585/mmwr.mm7218a3.
52 National Center for Health Statistics, National Vital Statistics System. Computer edits for mortality data, including separate section for fetal deaths effective 2020. NCHS Instruction Manual; part 11. 2020. Available from: https://www.cdc.gov/nchs/data/dvs/manuals/2020_PT11_B.pdf.
53 National Center for Health Statistics. Instruction manual, part 20: ICD–10 cause-of-death querying, 2013. 2013. Available from: https://www.cdc.gov/nchs/data/dvs/Instruction_Manual_revise20_2013.pdf.
54 Arias E, Eschbach K, Schauman WS, Backlund EL, Sorlie PD. The Hispanic mortality advantage and ethnic misclassification on US death certificates. Am J Public Health 2010 Apr 1;100 Suppl 1(Suppl 1):S171–7. Available from: https://ajph.aphapublications.org/doi/pdf/10.2105/AJPH.2008.135863.
55 Rosenberg HM, Maurer JD, Sorlie PD, Johnson NJ, MacDorman MF, Hoyert DL, et al. Quality of death rates by race and Hispanic origin: A summary of current research, 1999. National Center for Health Statistics. Vital Health Stat 2. 1999 Sept:(128):1–15. PMID: 10611854. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_128.pdf.
56 Sorlie PD, Rogot E, Johnson NJ. Validity of demographic characteristics on the death certificate. Epidemiology. 1992 Mar;3(2):181–4.1576225
57 Arias E, Xu JQ, Curtin S, Bastian B, Tejada-Vera B. Mortality Profile of the Non-Hispanic American Indian or Alaska Native Population, 2019. Natl Vital Stat Rep. 2021 Nov;70(12):1–27. PMID: 34842523. DOI: 10.15620/cdc:110370.
58 Mulry M. Summary of accuracy and coverage evaluation for Census 2000. Research Report Series Statistics #2006–3. Washington, DC: U.S. Census Bureau. 2006. Available from: https://www.census.gov/library/working-papers/2006/adrm/rrs2006-03.html.
59 Poe GS, Powell-Griner E, McLaughlin JK, Placek PJ, Thompson GB, Robinson K. Comparability of the death certificate and the 1986 National Mortality Followback Survey. National Center for Health Statistics. Vital Health Stat 2. 1993 Nov;(118):1–57. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_118.pdf.
60 U.S. Census Bureau. DSSD 2010 census coverage measurement memorandum series 2010–G–01. 2012. Available from: https://www2.census.gov/programs-surveys/decennial/2010/technical-documentation/methodology/g-series/g01.pdf.
61 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final Data for 2022. Natl Vital Stat Rep. 2024 Apr;73(2):1–56. PMID: 38625869. DOI: 10.15620/cdc:145588.
62 Sirken MG. Comparison of two methods of constructing abridged life tables by reference to a “standard” table. National Center for Health Statistics. Vital Health Stat 2. 1966 Feb;(4):1–19. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_004.pdf.
63 Anderson RN. Method for constructing complete annual U.S. life tables. National Center for Health Statistics. Vital Health Stat 2. 1999 Dec;(129):1–36. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_129.pdf.
64 National Center for Health Statistics. U.S. decennial life tables for 1989–91. Methodology of the National and State Life Tables; vol 1 no 2:1–13. 1998. Available from: https://www.cdc.gov/nchs/data/lifetables/life89_1_2.pdf.
65 Wei R, Curtin LR, Arias E, Anderson RN. U.S. decennial life tables for 1999–2001: State life tables. Natl Vital Stat Rep. 2012 Sep 14;60(9):1–66. PMID: 24979971. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr57/nvsr57_04.pdf.
66 Miniño AM, Murphy SL, Xu JQ, Kochanek KD. Deaths: Final data for 2008. Natl Vital Stat Rep. 2011 Dec 7;59(10):1–126. PMID: 22808755. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr59/nvsr59_10.pdf.
67 Arias E. United States life tables, 2008. Natl Vital Stat Rep. 2012 Sep 24;61(3):1–63. PMID: 24974590. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr61/nvsr61_03.pdf.
68 Kochanek KD, Maurer JD, Rosenberg HM. Causes of death contributing to changes in life expectancy: United States, 1984–89. National Center for Health Statistics. Vital Health Stat. 1994 May;20(23):1–37. Available from: https://www.cdc.gov/nchs/data/series/sr_20/sr20_023.pdf.
69 Arriaga EE. Changing trends in mortality decline during the last decades. In: Ruzicka L, Wunsch G, Kane P, editors. Differential mortality: Methodological issues and biosocial factors. Oxford, England: Clarendon Press;1989.
70 Arriaga EE. Measuring and explaining the change in life expectancies. Demography 1984 Feb;21(1):83–96.6714492
71 Miniño AM, Anderson RN, Fingerhut LA, Boudreault MA, Warner M. Deaths: injuries, 2002. Natl Vital Stat Rep. 2006 Jan 31;54(10):1–124. PMID: 16485447. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr54/nvsr54_10.pdf.
72 Sorlie PD, Johnson NJ. Validity of education information on the death certificate. Epidemiology. 1996 Jul;7(4):437–9. PMID: 8793373.8793373
73 Arias E, Liebler CA, Garcia MA, Sáenz R. Data impacts of changes in U.S. Census Bureau procedures for race and ethnicity data. SSM Popul Health. 2025 Jan 9; 29:101742. PMID: 39897609. DOI: 10.1016/j.ssmph.2024.101742.39897609
74 U.S. Census Bureau. American Community Survey, 2022 1-year ACS public use microdata sample. Available from: https://www2.census.gov/programs-surveys/acs/tech_docs/pums/2022ACS_PUMS_User_Guide.pdf.
75 U.S. Census Bureau. International data base. Population by single years of age and sex, 2022. 2023. Available from: https://www.census.gov/data-tools/demo/idb/#/dashboard?YR_ANIM=2022&FIPS_SINGLE=**&dashPages=DASH&COUNTRY_YEAR=2022&COUNTRY_YR_ANIM=2024.
76 Anderson RN, Rosenberg HM. Age standardization of death rates: Implementation of the year 2000 standard. Natl Vital Stat Rep. 1998 Oct 7;47(3):1–17. PMID: 9796247. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr47/nvs47_03.pdf.
77 Brillinger DR. The natural variability of vital rates and associated statistics. Biometrics. 1986 Dec; 42(4):693–734. PMID: 3814721.3814721
78 Fay MP, Feuer EJ. Confidence intervals for directly standardized rates: A method based on the gamma distribution. Stat Med 1997 Apr 15;16(7):791–801. PMID: 9131766.9131766
79 National Center for Health Statistics. Vital statistics of the United States: Mortality, 1999. Technical appendix. 2004:1–93. Available from: https://www.cdc.gov/nchs/data/statab/techap99.pdf.
80 Schenker N, Gentleman JF. On judging the significance of differences by examining the overlap between confidence intervals. Am Stat. 2001 Aug;55(3):182–6. Available from: https://www.jstor.org/stable/2685796?seq=1#page_scan_tab_contents.
81 Arnold SF. Mathematical statistics. Englewood Cliffs, NJ: Prentice Hall; 1990.

## Technical Notes

### Nature and sources of data

Data in this report are based on information from all death certificates filed in the 50 states and the District of Columbia (D.C.) and are processed by the National Center for Health Statistics (NCHS). Death certificates are completed by funeral directors, attending physicians, medical examiners, coroners, or other people legally authorized to certify deaths. Data for 2022 are based on records of deaths that occurred during 2022 and were received as of September 7, 2023. Data for earlier years can be obtained from the Centers for Disease Control and Prevention’s (CDC) WONDER database (14).

The U.S. Standard Certificate of Death, which the states use as a model, was revised in 2003 (7). Before 2003, the standard certificate of death had not been revised since 1989 (15). Beginning in 2018, all 50 states and D.C. used the 2003 revision of the U.S. Standard Certificate of Death for the entire year. During 2003–2017, both the 1989 and the 2003 standard certificates were used. For this transitional period, race and Hispanic ethnicity of decedents was reported using the 1977 Office of Management and Budget (OMB) guidelines (1989 certificate), which allowed the reporting of only one race and provided four choices, and the 1997 OMB guidelines (2003 certificate), which allowed the reporting of more than one race and provided five categories (7,8).

Data for Commonwealth of the Northern Mariana Islands (Northern Marianas), Guam, Puerto Rico, and U.S. Virgin Islands are included in tables showing data by state but are not included in U.S. totals. Data for American Samoa for the 2022 data year were not available at the time of file closing and, consequently, are not included in this report. In 2022, Guam, Northern Marianas, Puerto Rico, and U.S. Virgin Islands collected and reported death data using the 2003 revision of the U.S. Standard Certificate of Death. Mortality statistics are based on information submitted by the jurisdictions and coded by NCHS through the Vital Statistics Cooperative Program. For the 2022 data year, all states, D.C., New York City, Northern Marianas, and Puerto Rico submitted mortality medical data and demographic data in electronic data files to NCHS. Guam and U.S. Virgin Islands submitted copies of death certificates, from which NCHS entered and coded all medical data and demographic data.

Data for the entire United States refer to events occurring within the United States. Data shown for geographic areas are by place of residence. Beginning with 1970, mortality statistics for the United States exclude deaths of nonresidents of the United States. All data exclude fetal deaths.

Mortality statistics for Northern Marianas, Puerto Rico, and U.S. Virgin Islands exclude deaths of nonresidents for each area. For Guam, however, mortality statistics exclude deaths that occurred to nonresidents of Guam or the United States (50 states and D.C.).

### Cause-of-death classification

The mortality statistics presented in this report were compiled in accordance with World Health Organization (WHO) regulations, which specify that member countries classify and code causes of death in accordance with the current revision of the International Classification of Diseases (ICD). ICD provides the basic guidance used in virtually all countries to code and classify causes of death. Effective with deaths occurring in 1999, the United States began using the 10th revision of this classification (ICD–10) (33). For earlier years, causes of death were classified according to the revisions then in use: 1979–1998, Ninth Revision; 1968–1978, Eighth Revision, adapted for use in the United States; 1958–1967, Seventh Revision; and 1949–1957, Sixth Revision.

Changes in classification of causes of death due to these revisions may result in discontinuities in cause-of-death trends. Consequently, cause-of-death comparisons among revisions require consideration of comparability ratios and, where available, estimates of their standard errors (SEs). Comparability ratios between the Ninth and Tenth revisions, Eighth and Ninth revisions, Seventh and Eighth revisions, and Sixth and Seventh revisions may be found in other NCHS reports and independent tabulations (34–39).

ICD not only details disease classification but also provides definitions, tabulation lists, the format of the death certificate, and the rules for coding cause of death. Cause-of-death data presented in this publication were coded by procedures outlined in annual issues of the NCHS Instruction Manual (40,41). ICD includes rules for selecting the underlying cause of death and regulations on the use of ICD.

Before data year 1968, mortality medical data were based on manual coding of an underlying cause of death for each certificate, in accordance with WHO rules. Effective with data year 1968, NCHS converted to computerized coding of the underlying cause and manual coding of all causes (multiple causes) on the death certificate. In this system, called Automated Classification of Medical Entities (ACME) (42), multiple-cause codes are inputted into computer software that uses WHO rules to select the underlying cause. All cause-of-death data in this report are coded using ACME.

The ACME system is used to select the underlying cause of death for all death certificates in the United States. In addition, NCHS developed two computer systems as inputs to ACME. Beginning with 1990 data, the Mortality Medical Indexing, Classification, and Retrieval system (MICAR) (43) was introduced to automate the coding of multiple causes of death. In addition, MICAR provides more detailed information on the conditions reported on death certificates than is available through ICD code structure. Beginning with data year 1993, SuperMICAR (44), an enhancement of the MICAR system, was introduced, allowing for literal entry of the multiple cause-of-death text as reported by the certifier. This information is then automatically processed by the MICAR and ACME computer systems. Records that cannot be automatically processed by MICAR are manually multiple-cause coded and then further processed through ACME to determine the underlying cause of death. In 2022, SuperMICAR was used to process all of the country’s death records.

In 2022, NCHS began using MedCoder, a new system that integrates natural language processing and machine learning for coding multiple causes of death. This system replaced the Mortality Medical Data System (MMDS). MedCoder can code nearly 90% of records automatically, compared with less than 75% for the previous system. For more information, please visit: https://www.cdc.gov/nchs/nvss/medcoder.htm.

In this report, tabulations of cause-of-death statistics are based solely on the underlying cause of death. The underlying cause is defined by WHO as “the disease or injury which initiated the train of morbid events leading directly to death, or the circumstances of the accident or violence which produced the fatal injury” (4). The underlying cause is selected from the conditions entered by the medical certifier in the cause-of-death section of the death certificate. When more than one cause or condition is entered by the medical certifier, the underlying cause is determined by the sequence of conditions on the certificate, provisions of ICD, and associated selection rules and modifications. Generally, more medical information is reported on death certificates than is directly reflected in the underlying cause of death. This is captured in NCHS multiple cause-of-death statistics (45,46–47).

### Tabulation lists and cause-of-death ranking

Tabulation lists for ICD–10 are published in NCHS Instruction Manual, Part 9, “ICD–10 Cause-of-Death Lists for Tabulating Mortality Statistics” (updated October 2020 to include WHO updates to ICD–10 for data year 2020) (48). Two tabulation lists are used to rank leading causes of death (48): a) “List of 113 Selected Causes of Death, Enterocolitis due to Clostridium difficile, and COVID-19” (the title of which was modified in 2009 to include Enterocolitis due to Clostridium difficile and modified again in 2020 to include COVID-19), which is used for deaths of all ages; and b) “List of 130 Selected Causes of Infant Death,” which is used for infants. Not all causes in the 113 list of causes are rankable. Group titles of Major cardiovascular diseases (ICD–10 codes I00–I78) and Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified (R00–R99) are not ranked. In addition, category titles that begin with the words “other” and “all other” are not ranked to determine the leading causes of death. When one of the titles that represents a subtotal is ranked, for example, Tuberculosis (A16–A19), its component parts are not ranked, as in this case, Respiratory tuberculosis (A16) and Other tuberculosis (A17–A19). For the list of 130 causes of infant death, the same ranking procedures are used with two exceptions: 1) COVID-19 is included in the category Other and unspecified viral diseases but is not a separate rankable cause, and 2) the category of Major cardiovascular diseases is not on the list. More detail regarding ranking procedures can be found in “Deaths: Leading Causes for 2022” (2).

Leading cause-of-death trends discussed in this report are based on cause-of-death data according to ICD–10 for 1999–2022 and ICD–9 for the most comparable cause-of-death titles for 1979–1998.

Although, in some cases, categories from the “List of 113 Selected Causes of Death” are identical to those in the earlier “List of 72 Selected Causes of Death” used with ICD–9, caution must be used because many of these categories are not comparable even though the cause-of-death titles may be the same. Tables showing ICD–9 categories that are comparable with ICD–10 titles in the “List of 113 Selected Causes of Death” may be found in the reports, “Comparability of Cause of Death Between ICD–9 and ICD–10: Preliminary Estimates” (36) and “Deaths: Final Data for 1999” (49).

Trend data for 1979–1998 that are classified by ICD–9 but sorted into the “List of 113 Selected Causes of Death” developed for ICD–10 are available from the NCHS website: https://www.cdc.gov/nchs/data/statab/hist001r.pdf.

Revision of ICD and resulting changes in classification and rules for selecting the underlying cause of death have important implications for the analysis of mortality trends by cause of death. For some causes of death, the discontinuity in trend can be substantial (36–39). Consequently, considerable caution should be used in analyzing cause-of-death trends for periods of time that extend across more than one revision of ICD.

### Codes added or deleted in 2022

No codes were added or deleted from the list of valid underlying cause-of-death codes in 2022. Information on codes added or deleted in previous years is available from: https://www.cdc.gov/nchs/data/dvs/Part9InstructionManual2020-508.pdf (48).

### Codes for terrorism

Beginning with data for 2001, NCHS introduced categories *U01–*U03 for classifying and coding deaths due to acts of terrorism. The asterisks before the category codes indicate that they are not part of ICD–10. Deaths classified to the terrorism categories are included in the 113 causes of death list in the categories for Assault (homicide) and Intentional self-harm (suicide), and in the 130 causes of death list for infants in the category for Assault (homicide). Additional information on these new categories is available from: https://archive.cdc.gov/#/details?url=https://www.cdc.gov/nchs/icd/terrorism_code.htm. No deaths were assigned to terrorism codes in 2022. Only deaths to residents of the United States are included in this report.

In any given year, deaths resulting from acts of terrorism may not be identified as such if: a) information identifying an incident as an act of terrorism is not available to the certifier at the time of certification; b) the certificate is not updated with the information if it later becomes available; or c) official results of the investigation declaring the incident to be an act of terrorism have not yet been made public.

### COVID-19

COVID-19 (ICD–10 code U07.1) became an official new cause of death in 2020 after the first death from COVID-19 was reported in the United States. For people age 1 and older, COVID-19 was added as a rankable cause of death. For infants (younger than 1), COVID-19 was added to the cause-of-death category Other and unspecified viral diseases but is not considered as a separate rankable cause. In report tables showing 113 selected causes, COVID-19 was added to the bottom of the table.

Deaths assigned to COVID-19 may not reflect all deaths directly or indirectly due to COVID-19 because some deaths due to COVID-19 may not have been diagnosed, especially early in the pandemic, and some deaths may have been assigned to another, co-existing condition. Estimates of excess deaths—the difference between the observed number of deaths and the expected number of deaths—can provide information about the effect of the COVID-19 pandemic on mortality. Excess deaths include deaths directly or indirectly attributable to COVID-19. Estimates of excess deaths based on provisional data are available from: https://www.cdc.gov/nchs/nvss/vsrr/covid19/excess_deaths.htm (50). Provisional data are incomplete and may underestimate counts relative to final data, but they provide an early indication of shifts in mortality trends and can guide public health policies and interventions aimed at reducing mortality (51).

COVID-19 data in this report do not include deaths where COVID-19 may have been reported as a contributing cause but was not considered to be the underlying cause of death. For additional coding detail and guidelines, see: https://www.cdc.gov/nchs/covid19/coding-and-reporting.htm. Data are not adjusted for potential issues with diagnosis, testing, or reporting. Data in this report are final data and may differ from provisional data published previously (available from: https://www.cdc.gov/nchs/nvss/vsrr/covid19/index.htm).

### Enterocolitis due to Clostridium difficile

The number of deaths from Enterocolitis due to Clostridium difficile (C. difficile) (ICD–10 code A04.7) was 4,231 in 2022. Deaths from this cause increased dramatically from 793 deaths in 1999 to a high of 8,085 deaths in 2011 (14). Because of the increasing importance of this cause of death (21,22), beginning with data year 2006, C. difficile was added to the list of rankable causes.

### Quality of reporting and processing cause of death

The quality of mortality data is largely dependent on proper and thorough completion of death certificates by certifiers. Accuracy and completeness of information entered on death certificates can vary by state from year to year.

One index of the quality of reporting causes of death is the proportion of death certificates coded to Chapter XVIII—Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified (ICD–10 codes R00–R99). Although which deaths occur for which underlying causes are impossible to determine, the proportion coded to R00–R99 indicates the consideration given to the cause-of-death statement by the medical certifier. This proportion also may be used as a rough measure of the specificity of medical diagnoses made by the certifier in various areas. The percentage of all reported deaths in the United States assigned to Symptoms, signs and abnormal clinical and laboratory findings, not elsewhere classified, increased from 1.00% in 2021 to 1.04% in 2022.

Rules for coding a cause or causes of death may sometimes require modification when evidence suggests it will improve the quality of cause-of-death data. Before 1999, such modifications were made only when a new ICD revision was implemented. A process for updating ICD was introduced with ICD–10 that allows for midrevision changes. These changes, however, may affect comparability of data between years for selected causes of death.

Detail on coding and classification rule changes can be found in NCHS Instruction Manual, Part 2, available from: https://www.cdc.gov/nchs/nvss/instruction_manuals.htm (40–42). Although coding rule changes can impact the number of deaths assigned to a given code, other factors, such as increased use of a term by certifiers, can also influence changes from year to year. Trend data for causes of death affected by coding rule changes should be interpreted with caution.

### Rare causes of death

Selected causes of death considered to be of public health concern are supposed to be routinely confirmed by states according to agreed-upon procedures between state vital statistics programs and NCHS. These causes, termed “infrequent and rare causes of death,” are listed in the NCHS Instruction Manual, Parts 2a, 11, and 20 (40,52,53). In 2022, some states did not confirm some or all deaths from rare causes.

### Codes for dementia-related causes

Causes of death attributable to dementia-related mortality include ICD–10 codes F01, Vascular dementia; F03, Unspecified dementia; G30, Alzheimer disease; and G31, Other degenerative diseases of nervous system, not elsewhere classified.

### Codes for drug-induced deaths

Causes of death attributable to drug-induced mortality include ICD–10 codes D52.1, Drug-induced folate deficiency anemia; D59.0, Drug-induced hemolytic anemia; D59.2, Drug-induced nonautoimmune hemolytic anemia; D61.1, Drug-induced aplastic anemia; D64.2, Secondary sideroblastic anemia due to drugs and toxins; E06.4, Drug-induced thyroiditis; E16.0, Drug-induced hypoglycemia without coma; E23.1, Drug-induced hypopituitarism; E24.2, Drug-induced Cushing syndrome; E27.3, Drug-induced adrenocortical insufficiency; E66.1, Drug-induced obesity; selected codes from the ICD–10 title of Mental and behavioral disorders due to psychoactive substance use, specifically, F11.1–F11.5, F11.7–F11.9, F12.1–F12.5, F12.7–F12.9, F13.1–F13.5, F13.7–F13.9, F14.1– F14.5, F14.7–F14.9, F15.1–F15.5, F15.7–F15.9, F16.1–F16.5, F16.7–F16.9, F17.3–F17.5, F17.7–F17.9, F18.1–F18.5, F18.7–F18.9, F19.1–F19.5, and F19.7–F19.9; G21.1, Other drug-induced secondary parkinsonism; G24.0, Drug-induced dystonia; G25.1, Drug-induced tremor; G25.4, Drug-induced chorea; G25.6, Drug-induced tics and other tics of organic origin; G44.4, Drug-induced headache, not elsewhere classified; G62.0, Drug-induced polyneuropathy; G72.0, Drug-induced myopathy; I95.2, Hypotension due to drugs; J70.2, Acute drug-induced interstitial lung disorders; J70.3, Chronic drug-induced interstitial lung disorders; J70.4, Drug-induced interstitial lung disorder, unspecified; K85.3, Drug-induced acute pancreatitis; L10.5, Drug-induced pemphigus; L27.0, Generalized skin eruption due to drugs and medicaments; L27.1, Localized skin eruption due to drugs and medicaments; M10.2, Drug- induced gout; M32.0, Drug-induced systemic lupus erythematosus; M80.4, Drug-induced osteoporosis with pathological fracture; M81.4, Drug-induced osteoporosis; M83.5, Other drug-induced osteomalacia in adults; M87.1, Osteonecrosis due to drugs; R50.2, Drug-induced fever; R78.1, Finding of opiate drug in blood; R78.2, Finding of cocaine in blood; R78.3, Finding of hallucinogen in blood; R78.4, Finding of other drugs of addictive potential in blood; R78.5, Finding of psychotropic drug in blood; X40–X44, Accidental poisoning by and exposure to drugs, medicaments and biological substances; X60–X64, Intentional self-poisoning (suicide) by and exposure to drugs, medicaments and biological substances; X85, Assault (homicide) by drugs, medicaments and biological substances; and Y10–Y14, Poisoning by and exposure to drugs, medicaments and biological substances, undetermined intent. Drug-induced causes exclude unintentional injuries, homicide, and other causes indirectly related to drug use, as well as newborn deaths associated with the mother’s drug use.

Codes for drug-overdose causes—Causes of death attributable to drug overdose are a subcategory of drug-induced causes. Drug-overdose mortality includes ICD–10 codes X40–X44, X60–X64, X85, and Y10–Y14.

### Codes for alcohol-induced deaths

Causes of death attributable to alcohol-induced mortality include ICD–10 codes E24.4, Alcohol-induced pseudo-Cushing syndrome; F10, Mental and behavioral disorders due to alcohol use; G31.2, Degeneration of nervous system due to alcohol; G62.1, Alcoholic polyneuropathy; G72.1, Alcoholic myopathy; I42.6, Alcoholic cardiomyopathy; K29.2, Alcoholic gastritis; K70, Alcoholic liver disease; K85.2, Alcohol-induced acute pancreatitis; K86.0, Alcohol-induced chronic pancreatitis; R78.0, Finding of alcohol in blood; X45, Accidental poisoning by and exposure to alcohol; X65, Intentional self-poisoning by and exposure to alcohol; and Y15, Poisoning by and exposure to alcohol, undetermined intent. Alcohol-induced causes exclude unintentional injuries, homicides, and other causes indirectly related to alcohol use, as well as newborn deaths associated with maternal alcohol use.

### Codes for firearm-related deaths

Causes of death attributable to firearm-related injuries include ICD–10 codes *U01.4, Terrorism involving firearms (homicide); W32–W34, Accidental discharge of firearms; X72–X74, Intentional self- harm (suicide) by discharge of firearms; X93–X95, Assault (homicide) by discharge of firearms; Y22–Y24, Discharge of firearms, undetermined intent; and Y35.0, Legal intervention involving firearm discharge. Deaths from firearm-related injuries exclude deaths due to explosives and other causes indirectly related to firearms.

### Hispanic origin and race

The 2003 revision of the U.S. Standard Certificate of Death allows the reporting of more than one race (multiple races) (7). This change was implemented to reflect the increasing diversity of the U.S. population and to be consistent with the decennial census and the 1997 “Revisions to the Standards for the Classification of Federal Data on Race and Ethnicity,” issued by OMB (8). This revision replaced standards that were issued in 1977 (10). The new standards mandate the collection of more than one race where applicable, for federal data (8) and require the collection of information on a minimum set of five races (more than the minimum number of race categories are reported on death certificates) (7). Multiple race includes any combination of White, Black or African American, American Indian and Alaska Native, Asian, and Native Hawaiian or Other Pacific Islander. If two or more specific subgroups are reported on a death certificate and both subgroups fall under the same larger category, such as Korean and Chinese, those subgroups count as a single race (in this case, Asian) rather than as multiple races.

The number of states reporting multiple race increased, from 7 states in 2003 to all 50 states and the District of Columbia by 2018 (Table I). In 2022, more than one race was reported for 0.6% of decedents of non-Hispanic origin and for 0.9% of decedents of Hispanic origin (Table II). Although still uncommon, multiple races were reported more often for younger decedents than for older decedents (3.6% of decedents younger than age 25 compared with 1.0% of decedents ages 25–64 and 0.4% of decedents age 65 and older) (14).

Table I Year state started reporting multiple race and year state began using the revised standard certificate of death: Each state

Area | Year^1^ state began reporting multiple race | Year state began using 2003 standard certificate | Area | Year^1^ state began reporting multiple race | Year statebegan using 2003 standard certificate
Alabama | 2016 | 2016 | Montana | 2003 | 2003
Alaska | 2014 | 2014 | Nebraska | 2005 | 2005
Arizona | 2010 | 2010 | Nevada | 2008 | 2008
Arkansas | 2008 | 2008 | New Hampshire | ^9^2004 | ^10^2004
California | 2003 | 2003 | New Jersey | 2004 | 2004
Colorado | 2015 | 2015 | New Mexico | 2006 | 2006
Connecticut | 2005 | 2005 | New York | 2003 | 2003
Delaware | 2007 | 2007 | North Carolina | 2014 | 2014
District of Columbia | ^2^2005 | ^3^2005 | North Dakota | 2008 | 2008
Florida | 2005 | 2005 | Ohio | 2007 | 2007
Georgia | 2008 | 2008 | Oklahoma | 2004 | 2004
Hawaii | 2003 | 2014 | Oregon | 2006 | 2006
Idaho | 2003 | 2003 | Pennsylvania | 2012 | 2012
Illinois | 2008 | 2008 | Rhode Island | 2006 | 2006
Indiana | 2008 | 2008 | South Carolina | 2005 | 2005
Iowa | 2011 | 2011 | South Dakota | 2004 | 2004
Kansas | 2005 | 2005 | Tennessee | 2012 | 2012
Kentucky | ^4^2010 | ^5^2010 | Texas | 2006 | 2006
Louisiana | ^4^2012 | ^5^2012 | Utah | 2005 | 2005
Maine | 2003 | ^6^2010 | Vermont | ^4^2008 | ^5^2008
Maryland | 2015 | 2015 | Virginia | ^11^2014 | ^12^2014
Massachusetts | ^7^2014 | ^8^2014 | Washington | 2004 | 2004
Michigan | 2004 | 2004 | West Virginia | ^7^2017 | ^8^2017
Minnesota | 2004 | ^3^2011 | Wisconsin | 2003 | ^5^2013
Mississippi | 2012 | 2012 | Wyoming | 2004 | 2004
Missouri | 2010 | 2010
^1^Indicates year in which National Center for Health Statistics first received multiple-race data from each state, although the state may have begun collecting such data at an earlier date.^2^Began reporting multiple race in March.^3^Began implementing revised certificate in March.^4^Began reporting multiple race in July.^5^Began implementing revised certificate in July.^6^Began implementing revised certificate in June.^7^Began implementing revised certificate in September.^8^Began reporting multiple race in September.^9^Began reporting multiple race in mid-April.^10^Began implementing revised certificate in mid-April.^11^Began reporting multiple race in November.^12^Began implementing revised certificate in November.
SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Table II Deaths, by Hispanic origin and race: United States, 2022

[Data exclude deaths with origin not stated or not classifiable. Records with race not stated or not classifiable are imputed; see Technical Notes in this report]

Hispanic origin and race | Deaths | Percent of non-Hispanic deaths^1^ | Hispanic origin and race | Deaths | Percent of Hispanic deaths^1^
Non-Hispanic | 2,994,727 | 100.0 | Hispanic | 275,684 | 100.0
One race | 2,977,823 | 99.4 | One race | 273,099 | 99.1
American Indian and Alaska Native (AIAN) | 23,613 | 0.8 | AIAN | 1,705 | 0.6
Asian | 89,591 | 3.0 | Asian | 886 | 0.3
Black | 411,934 | 13.8 | Black | 5,353 | 1.9
Native Hawaiian or Other Pacific Islander (NHOPI) | 4,592 | 0.2 | Native Hawaiian or Other Pacific Islander (NHOPI) | 315 | 0.1
White | 2,448,093 | 81.7 | White | 264,840 | 96.1
Two or more races | 16,904 | 0.6 | Two or more races | 2,585 | 0.9
Two races | 15,842 | 0.5 | Two races | 2,365 | 0.9
AIAN and Asian | 203 | 0.0 | AIAN and Asian | 31 | 0.0
AIAN and NHOPI | 44 | 0.0 | AIAN and NHOPI | 4 | 0.0
AIAN and White | 5,997 | 0.2 | AIAN and White | 936 | 0.3
Asian and NHOPI | 1,145 | 0.0 | Asian and NHOPI | 27 | 0.0
Asian and White | 2,975 | 0.1 | Asian and White | 574 | 0.2
Black and AIAN | 967 | 0.0 | Black and AIAN | 58 | 0.0
Black and Asian | 426 | 0.0 | Black and Asian | 22 | 0.0
Black and NHOPI | 134 | 0.0 | Black and NHOPI | 7 | 0.0
Black and White | 2,969 | 0.1 | Black and White | 580 | 0.2
NHOPI and White | 982 | 0.0 | NHOPI and White | 126 | 0.0
Three races | 1,047 | 0.0 | Three races | 213 | 0.1
AIAN, Asian, and NHOPI | 5 | 0.0 | AIAN, Asian, and NHOPI | 1 | 0.0
AIAN, Asian, and White | 36 | 0.0 | AIAN, Asian, and White | 16 | 0.0
AIAN, NHOPI, and White | 24 | 0.0 | AIAN, NHOPI, and White | 5 | 0.0
Asian, NHOPI, and White | 643 | 0.0 | Asian, NHOPI, and White | 115 | 0.0
Black, AIAN, and Asian | 16 | 0.0 | Black, AIAN, and Asian | 3 | 0.0
Black, AIAN, and NHOPI | 3 | 0.0 | Black, AIAN, and NHOPI | – | –
Black, AIAN, and White | 232 | 0.0 | Black, AIAN, and White | 54 | 0.0
Black, Asian, and NHOPI | 15 | 0.0 | Black, Asian, and NHOPI | 2 | 0.0
Black, Asian, and White | 63 | 0.0 | Black, Asian, and White | 16 | 0.0
Black, NHOPI, and White | 10 | 0.0 | Black, NHOPI, and White | 1 | 0.0
Four races | 15 | 0.0 | Four races | 7 | 0.0
AIAN, Asian, NHOPI, and White | 4 | 0.0 | AIAN, Asian, NHOPI, and White | 4 | 0.0
Black, AIAN, Asian, and NHOPI | – | – | Black, AIAN, Asian, and NHOPI | – | –
Black, AIAN, Asian, and White | 7 | 0.0 | Black, AIAN, Asian, and White | 2 | 0.0
Black, AIAN, NHOPI, and White | 1 | 0.0 | Black, AIAN, NHOPI, and White | – | –
Black, Asian, NHOPI, and White | 3 | 0.0 | Black, Asian, NHOPI, and White | 1 | 0.0
Five races | – | – | Five races | – | –
Black, AIAN, Asian, NHOPI, and White | – | – | Black, AIAN, Asian, NHOPI, and White | – | –

0.0 Quantity more than zero but less than 0.05.

– Quantity zero.

^1^Percentages may not add to 100 due to rounding.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

During 2003–2017, both the 1989 and the 2003 standard death certificates were used. For this transitional period, states using the1989 death certificate reported the race and Hispanic ethnicity of decedents based on the OMB 1977 guidelines, which allowed the reporting of only one race and provided four choices: White, Black, American Indian and Alaskan Native, and Asian or Pacific Islander. Under these standards, data for Asian or Pacific Islander people were collected as a single group; that is, data for Asian people were not reported separately from Pacific Islander people (10,15). States using the 2003 death certificate reported the race and Hispanic ethnicity of decedents based on the OMB 1997 guidelines, which allowed the reporting of more than one race and provided five categories (7,8). These guidelines provide for the reporting of Asian people separately from Native Hawaiian or Other Pacific Islander people (8). Jurisdictions adopted the 2003 standard certificate at different times throughout the period 2003–2017. To provide consistent mortality statistics by Hispanic origin and race during this period, multiple-race data for states that had adopted the 2003 standard certificate were bridged back to the 1977 OMB standard single-race categories.

Beginning in 2018, all states collected data on race according to the 1997 OMB guidelines, so the use of the bridged-race process was no longer necessary. In 2018, the new race categories became the official categories for reporting race. For comparative purposes, data by both single- and bridged-race were tabulated through data year 2020 (30). Beginning with the 2021 data year, bridged-race estimates are no longer produced, and bridged race data for earlier years are no longer presented in this report.

Hispanic origin and race are two distinct attributes and are reported separately on the death certificate. As a result, data shown by Hispanic origin and race are based on a combination of the two attributes for the non-Hispanic population. Data shown for the Hispanic population include people of any race.

Quality of race and Hispanic-origin data—Death rates for Hispanic, American Indian and Alaska Native non-Hispanic, Asian non-Hispanic, and Native Hawaiian or Other Pacific Islander non-Hispanic populations are affected by inconsistencies in reporting Hispanic origin or race on the death certificate compared with censuses, surveys, and birth certificates. Studies have shown underreporting on death certificates of non-Hispanic and Hispanic decedents, as well as undercounts of these groups in censuses (16,54–56).

A number of studies have been conducted on the reliability of Hispanic origin and race reported on the death certificate by comparing it with Hispanic origin and race reported on another data collection instrument, such as a census or survey (16,54–56). Inconsistencies may arise because of differences in who provides race and ethnicity information on the compared records. Race and Hispanic-origin information on the death certificate is reported by a funeral director as provided by an informant or, in the absence of an informant, on the basis of observation. In contrast, Hispanic origin and race in the census or the U.S. Census Bureau’s American Community Survey (ACS) is obtained while the person is alive; in these cases, race and ethnicity is self-reported or reported by another member of the household familiar with the person and, consequently, may be considered more valid. A high level of agreement between the death certificate and the census or survey report is essential to assure unbiased death rates by race and ethnicity.

Using the National Longitudinal Mortality Study, Arias et al. examined the reliability of Hispanic origin and race reported on more than 559,000 death certificates compared with that reported on a total of 38 Current Population Surveys (CPSs) conducted by the U.S. Census Bureau for 1979–2011 (16,54). Agreement between the two sources was found to be excellent for the White non-Hispanic and Black non-Hispanic populations, both exhibiting CPS-to-death certificate ratios of 1.00. On the other hand, substantial differences were found for other race and ethnicity groups. The ratio of CPS-to-death certificates was found to be 1.33 for the American Indian and Alaska Native non-Hispanic population and 1.03 for the Asian or Other Pacific Islander non-Hispanic population, indicating net underreporting on death certificates of 33% for American Indian and Alaska Native non-Hispanic and 3% for Asian or Other Pacific Islander non-Hispanic. Using the new race standard, Asian and Pacific Islander are separate categories. The ratio of deaths for CPS-to-death certificates for Hispanic people was found to be 1.03, indicating a net underreporting on death certificates for the Hispanic population of 3%. The net effect of misclassification is an underestimation of deaths and death rates for some race–ethnicity populations.

A new study on race and Hispanic-origin misclassification for the American Indian and Alaska Native non-Hispanic population found similar results as the earlier study, with a misclassification rate of 1.34. The study was based on an extract of the 2010 Census Edited File–Census Unedited File Match File containing records for people classified as American Indian and Alaska Native alone or in combination with another race in the 2010 decennial census linked to the National Death Index to identify decedents for April 1, 2010, to December 31, 2011 (57).

In addition, undercoverage of minority groups in the census and resultant population estimates introduces biases into death rates by Hispanic origin and race (16,54–56,58,59). Unlike the 1990 census, coverage error in the 2000 census was found to be statistically significant only for the White non-Hispanic population (overcounted by about 1.13%) and Black non-Hispanic population (undercounted by about 1.84%) (58). Overall, the 2010 census coverage error was minor, with a net overcount of 0.01%. The net undercounts were statistically different from zero for the following populations: Black non-Hispanic (2.07%), White non-Hispanic (–0.84%), Hispanic (1.54%), and on-reservation American (4.88%) populations. The net undercounts were not statistically different from zero for the Asian non-Hispanic (0.08%), Native Hawaiian or Pacific Islander (1.34%), and off-reservation American Indian (–1.95%) populations (60).

Data year 1997 was the first year in which mortality data by Hispanic origin were available for the entire United States.

Mortality data presented by specified Hispanic subgroup for the United States include Central American, Cuban, Dominican, Mexican, Puerto Rican, South American, and Other Hispanic populations. Data by specified Hispanic populations are affected by whether a state submits literal text to the National Center for Health Statistics (NCHS), making it possible to identify decedents as being of Central American, Cuban, Dominican, Mexican, Puerto Rican, or South American.

Numbers of deaths and death rates discussed in this report are not adjusted for misclassification of ethnicity and race. These data are consistent with data in the general mortality file as reported by the jurisdictions. However, to illustrate the effect of ethnicity and race misclassification, Table III presents classification ratios by Hispanic origin and race, age, and sex and Table IV presents age-adjusted rates by Hispanic origin and race and sex, both unadjusted and adjusted for ethnicity–race misclassification. Classification ratios and age-adjusted death rates adjusted for misclassification of Hispanic origin and race for the Native Hawaiian or Other Pacific Islander population were not produced because the data needed to evaluate ethnicity and race misclassification on death certificates for this population are not currently available.

Table III Classification ratio and standard error, by Hispanic origin and race, age, and sex

[Standard errors are shown in parentheses below each classification ratio]

Age | Hispanic^1^ | | | Non-Hispanic^1^
Age | Hispanic^1^ | | | American Indian and Alaska Native | | | Asian^2^ | | | Black | | | White
Age | Total | Male | Female | Total | Male | Female | Total | Male | Female | Total | Male | Female | Total | Male | Female
All ages | 1.0329 | 1.0362 | 1.0294 | 1.3354 | 1.3488 | 1.3197 | 1.0331 | 1.0480 | 1.0171 | 1.0047 | 1.0041 | 1.0053 | 0.9995 | 0.9993 | 0.9997
| (0.005) | (0.007) | (0.007) | (0.007) | (0.010) | (0.011) | (0.009) | (0.013) | (0.012) | (0.002) | (0.002) | (0.002) | (0.000) | (0.001) | (0.000)
0 | *1.7054 | *1.0000 | *2.1519 | 0.9630 | *0.9444 | *1.0000 | --- | --- | --- | *1.0000 | *1.0000 | *1.0000 | *1.0000 | *1.0000 | *1.0000
| (0.896) | (0.000) | (1.821) | (0.132) | (0.181) | (0.161) | … | … | … | (0.000) | (0.000) | (0.000) | (0.000) | (0.000) | (0.000)
1–14 | 0.9905 | 0.9659 | *1.0299 | 1.1243 | 1.1546 | 1.0833 | *0.8655 | *0.8426 | *1.0000 | 1.0266 | 0.9379 | *1.1751 | 0.9918 | 1.0755 | 0.8770
| (0.125) | (0.181) | (0.143) | (0.051) | (0.069) | (0.074) | (0.131) | (0.154) | (0.000) | (0.058) | (0.065) | (0.123) | (0.037) | (0.049) | (0.056)
15–24 | 0.9668 | 0.9325 | 1.0604 | 1.1462 | 1.1201 | 1.2190 | 1.2285 | *1.4276 | *0.9721 | 1.0248 | 1.0215 | 1.0343 | 0.9976 | 1.0019 | 0.9869
| (0.046) | (0.055) | (0.079) | (0.029) | (0.033) | (0.056) | (0.294) | (0.508) | (0.254) | (0.020) | (0.019) | (0.055) | (0.010) | (0.011) | (0.020)
25–34 | 1.0354 | 1.0401 | 1.0232 | 1.1375 | 1.1557 | 1.1033 | 1.1527 | 1.0967 | *1.2648 | 0.9855 | 0.9770 | 1.0008 | 1.0021 | 1.0034 | 0.9994
| (0.041) | (0.043) | (0.094) | (0.025) | (0.032) | (0.040) | (0.106) | (0.102) | (0.248) | (0.009) | (0.011) | (0.015) | (0.006) | (0.007) | (0.013)
35–44 | 1.0434 | 1.0645 | 1.0066 | 1.1799 | 1.1815 | 1.1772 | 1.0338 | 1.0459 | 1.0125 | 1.0062 | 1.0073 | 1.0048 | 0.9980 | 0.9997 | 0.9951
| (0.025) | (0.035) | (0.028) | (0.022) | (0.027) | (0.036) | (0.066) | (0.090) | (0.092) | (0.007) | (0.010) | (0.012) | (0.003) | (0.004) | (0.005)
45–54 | 1.0584 | 1.0372 | 1.0953 | 1.3915 | 1.3913 | 1.3916 | 1.0699 | 1.1123 | 1.0113 | 1.0002 | 1.0019 | 0.9982 | 0.9969 | 0.9965 | 0.9976
| (0.018) | (0.021) | (0.033) | (0.021) | (0.027) | (0.033) | (0.040) | (0.054) | (0.059) | (0.004) | (0.007) | (0.005) | (0.002) | (0.002) | (0.003)
55–64 | 1.0571 | 1.0517 | 1.0659 | 1.4281 | 1.4547 | 1.3917 | 1.0274 | 1.0694 | 0.9784 | 1.0003 | 0.9965 | 1.0046 | 0.9994 | 0.9992 | 0.9997
| (0.013) | (0.017) | (0.022) | (0.019) | (0.026) | (0.029) | (0.028) | (0.044) | (0.035) | (0.004) | (0.006) | (0.005) | (0.001) | (0.002) | (0.002)
65–74 | 1.0295 | 1.0485 | 1.0072 | 1.3654 | 1.4244 | 1.2980 | 1.0845 | 1.0841 | 1.0850 | 1.0062 | 1.0055 | 1.0070 | 0.9967 | 0.9967 | 0.9966
| (0.010) | (0.014) | (0.015) | (0.017) | (0.025) | (0.023) | (0.022) | (0.030) | (0.033) | (0.003) | (0.005) | (0.005) | (0.001) | (0.001) | (0.001)
75–84 | 1.0192 | 1.0188 | 1.0196 | 1.3099 | 1.3367 | 1.2852 | 1.0305 | 1.0328 | 1.0281 | 1.0057 | 1.0057 | 1.0058 | 1.0004 | 1.0003 | 1.0004
| (0.009) | (0.013) | (0.013) | (0.017) | (0.025) | (0.022) | (0.014) | (0.022) | (0.017) | (0.003) | (0.005) | (0.004) | (0.001) | (0.001) | (0.001)
85–94 | 1.0208 | 1.0313 | 1.0137 | 1.3845 | 1.3807 | 1.3870 | 0.9962 | 0.9983 | 0.9944 | 1.0110 | 1.0155 | 1.0086 | 1.0008 | 1.0007 | 1.0009
| (0.011) | (0.018) | (0.014) | (0.024) | (0.038) | (0.032) | (0.015) | (0.020) | (0.021) | (0.004) | (0.007) | (0.005) | (0.001) | (0.001) | (0.001)
95 and older | 1.0732 | 1.0509 | 1.0842 | 1.3951 | 1.3043 | 1.4240 | 0.9755 | 1.0238 | 0.9405 | 0.9980 | 1.0070 | 0.9954 | 1.0005 | 0.9995 | 1.0008
| (0.025) | (0.034) | (0.033) | (0.052) | (0.098) | (0.062) | (0.039) | (0.045) | (0.057) | (0.010) | (0.029) | (0.010) | (0.001) | (0.003) | (0.001)
* Ratio does not meet National Center for Health Statistics standards of reliability; either the unweighted number of Current Population Survey deaths, the unweighted number of death certificate deaths, or both are based on fewer than 20 deaths.--- Data not available.… Category not applicable.^1^Classification ratios for the Hispanic and non-Hispanic race groups (Asian, Black, and White) are based on the National Longitudinal Mortality Study data (see: https://www.cdc.gov/nchs/data/series/sr_02/sr02_172.pdf). Classification ratios for the American Indian and Alaska Native non-Hispanic population are based on the Census AIAN Extract–Mortality Linked Data (see: https://www.cdc.gov/nchs/data/nvsr/nvsr70/NVSR70-12.pdf).^2^Classification ratios for the Asian non-Hispanic race group were estimated based on combined data for the Asian and Pacific Islander non-Hispanic groups due to data availability. However, the ratios reflect misclassification predominantly among the Asian component, which makes up more than 95% of the combined group.
SOURCES: The validity of race and Hispanic-origin reporting on death certificates in the United States: An update. National Center for Health Statistics. Vital Health Stat 2(172). 2016, and Mortality profile of the non-Hispanic American Indian or Alaska Native population, 2019. National Vital Statistics Reports, vol 70 no12. National Center for Health Statistics. 2021. DOI: https://dx.doi.org/10.15620/cdc:110370.

Table IV Age-adjusted death rate, unadjusted and adjusted for race–ethnicity misclassification, by Hispanic origin and race, and sex: United States, 2022

[Hispanic origin and race categories are consistent with 1997 Office of Management and Budget standards]

Hispanic origin and race and sex | Age-adjusted rate^1^
Hispanic origin and race and sex | Unadjusted^2^ | Adjusted^3^
Hispanic, total^4^ | 614.7 | 633.9
Male | 748.8 | 774.2
Female | 498.4 | 512.9
Non-Hispanic, single race^5^:
American Indian and Alaska Native | 947.9 | 1,249.8
Male | 1,084.3 | 1,444.1
Female | 816.1 | 1,063.6
Asian | 417.5 | 430.5
Male | 501.7 | 522.2
Female | 350.7 | 354.9
Black | 1,002.8 | 1,007.8
Male | 1,257.5 | 1,263.3
Female | 809.0 | 813.2
White | 822.2 | 821.7
Male | 972.1 | 971.9
Female | 692.7 | 691.9

^1^Rates per 100,000 U.S. standard population. For method of computation, see Technical Notes in this report.

^2^Data are not adjusted for race and Hispanic misclassification on death certificates; see Technical Notes. Rates are consistent with rates in other tables shown in this report.

^3^Data are adjusted for race and Hispanic-origin misclassification on death certificates; see Technical Notes. Rates may differ from rates in other tables shown in this report.

^4^Includes people of Hispanic origin of any race; see Technical Notes.

^5^Only one race was reported on the death certificate; see Technical Notes.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Hispanic origin not stated or not classifiable and race not stated or not classifiable—In 2022, death records with Hispanic origin not stated or not classifiable were not imputed and accounted for 0.3% of all records. Records with race not stated or not classifiable (1.4% of all records) were imputed to one of the five single-race categories by assigning the record a single-race value based on the last single-race record processed.

Infant and maternal mortality rates—Infant and maternal deaths in this report are tabulated by the Hispanic origin and race of the decedent. Live births, the denominators of infant and maternal mortality rates, are tabulated by Hispanic origin and race of mother.

In 2022, multiple race was reported on the revised birth certificates of all 50 states, the District of Columbia, Guam, Northern Marianas, Puerto Rico, and U.S. Virgin Islands using the 2003 revision of the U.S. Standard Certificate of Birth (61).

IMRs by Hispanic origin and race are based on numbers of resident infant deaths by Hispanic origin and race and numbers of resident live births by Hispanic origin and race of mother for the United States. In computing IMRs, deaths and live births of unknown or not classifiable origin are not distributed among the specified Hispanic and non-Hispanic groups. In the United States in 2022, the percentage of infant deaths of unknown origin was 1.1% (Table 2), and the percentage of live births to mothers of unknown origin was 1.0% (61).

Small numbers of infant deaths for specific Hispanic-origin groups result in IMRs subject to relatively large random variation (see “Random variation”).

IMRs calculated from the general mortality file for specified Hispanic origin and race contain errors because of reporting problems that affect the classification of Hispanic origin and race on the birth and death certificates for the same infant. IMRs by specified Hispanic origin and race are more accurate when based on the linked file of infant deaths and live births (31). The linked file computes IMRs using the Hispanic origin and race of the mother from the birth certificate in both the numerator and denominator of the rate. In addition, the mother’s Hispanic origin and race from the birth certificate are considered to be more accurately reported than the infant’s Hispanic origin and race from the death certificate. On the birth certificate, Hispanic origin and race are generally reported by the mother at the time of delivery, whereas on the death certificate, the infant’s Hispanic origin and race are reported by an informant, usually the mother but sometimes the funeral director.

Estimates of reporting errors have been made by comparing rates based on the linked files with those in which the infant’s Hispanic origin and race are based on information from the death certificate (31,55).

### Life tables

The life table provides a comprehensive measure of the effect of mortality on life expectancy. It is composed of sets of values showing the mortality experience of a hypothetical group of infants born at the same time and subject throughout their lifetime to the age-specific death rates of a particular time period, usually a given year. Before data year 1997, U.S. life tables were abridged and constructed by reference to a standard table (62). In addition, the age range for these life tables was limited to 5-year age groups ending with age group 85 and older. Beginning with final data reported for 1997, complete life tables were constructed by single years of age extending to age 100 (63), using a methodology similar to that of the 1989–1991 decennial life tables (64). The methodology was again revised for data years 2000–2007 using a methodology similar to that of the 1999–2001 decennial life tables (65).

Research into the methodology used for the 1999–2001 decennial life tables, which was applied to the 2000–2007 annual life tables, revealed that it is not necessary to model (or “smooth”) the probabilities of death beginning at age 66. The observed blended vital statistics and Medicare data for ages 66–85 are robust enough and do not require additional smoothing. Beginning with final data reported for 2008 (66), the life table methodology was refined by changing the smoothing technique used to estimate the life table functions at the oldest ages. Beginning with the 2008 data year, the methodology used to produce the life tables does not model the probabilities of death beginning at age 66, but rather at ages above 85 or so. See “United States Life Tables, 2008” for a detailed description of the new methodology (67). Life table data shown in this report for data years 2001–2022 are based on the new methodology.

Because life table values presented in this report for 2001–2009 were re-estimated using the new methodology and revised 2001–2009 intercensal population estimates based on the 2010 decennial census, the values may differ from those previously published in annual final mortality and life table reports. Historically, NCHS has produced annual life tables by race, including the White and Black populations, regardless of Hispanic origin, but did not produce life tables for other racial or ethnic groups. Beginning with data year 2006 (originally published elsewhere) (18), NCHS began producing life tables for the Hispanic, Black non-Hispanic, and White non-Hispanic populations, after conducting research into the quality of ethnicity and race reporting on death certificates and developing methodologies to correct for misclassification of these populations on death certificates (16,54). Beginning with data year 2019, life tables for the American Indian and Alaska Native non-Hispanic and Asian non-Hispanic populations were added to the annual life tables series. A new data source was used to evaluate the quality of ethnicity and race reporting and generate adjustment factors for the American Indian and Alaska Native population (57). Life tables for the Asian non-Hispanic population were produced using the same methodology as that used for the American Indian and Alaska Native non-Hispanic population following the transition to the 1997 OMB standard for the collection of race and ethnicity data which disaggregated the Asian and Native Hawaiian or Other Pacific Islander populations (8). These methods that adjust for misclassification are applied to the production of the life tables, but not to the death rates shown throughout this report.

Race-specific life tables for 2018 through 2022 presented in this report are based on the new OMB standard and show estimates for single-race groups. These estimates may not be comparable to those of previous years that are based on bridged-race groups. Estimates for bridged-race categories were discontinued in data year 2021. The category, “Hispanic” is consistent with previous reports, and trend data for the Hispanic population are not affected by the race category changes.

Although the life table methodology used produces complete life tables (by single years of age), the life table data shown in this report are summarized in 5-year age groupings.

### Causes of death contributing to changes in life expectancy

A life table partitioning technique was used to estimate causes of death contributing to changes in life expectancy in this report. The method partitions changes into component additive parts and identifies the causes of death having the greatest influence, positive or negative, on changes in life expectancy (68–70).

### Injury mortality by mechanism and intent

Injury mortality data are presented using the external cause-of-injury mortality matrix for ICD–10 (Table 14). In this framework, cause-of-injury deaths are organized principally by mechanism (such as firearm or poisoning), and secondarily by manner or intent of death (such as unintentional, suicide, or homicide).

The number of deaths for selected causes in this framework may differ from those shown in tables that use the standard mortality tabulation lists. Following WHO conventions, standard mortality tabulations (Table 9) present external causes of death (ICD–10 codes *U01–*U03 and V01–Y89); in contrast, the matrix (Table 14) excludes deaths classified as Complications of medical and surgical care (Y40–Y84 and Y88). For additional information on injury data presented in this framework, see “Deaths: Injuries, 2002,” available from: https://www.cdc.gov/nchs/data/nvsr/nvsr54/nvsr54_10.pdf (71). Data for later years are available through CDC WONDER (https://wonder.cdc.gov/) or through CDC WISQARS (https://www.cdc.gov/injury/wisqars/index.html). Implementation of changes to ICD–10 may affect the matrix, requiring modification of codes in selected categories. No changes were made to the matrix in 2022. For more information on the latest ICD–10 external cause-of-injury codes included in the matrix, see https://www.cdc.gov/nchs/injury/injury_tools.htm.

### Marital status

Mortality data by marital status are generally of high quality. A study of death certificate data using the 1986 National Mortality Followback Survey showed a high level of consistency in reporting marital status (59).

Although Table 13 shows age-specific death rates by marital status for age group 15–24, these rates are not included in the computation of the age-adjusted rate because of their high variability, particularly for the widowed population. Furthermore, age groups 75–84 and 85 and older are combined because of high variability in death rates among those age 85 and older, particularly for the never-married population.

### Educational attainment

Table 14 presents mortality data by educational attainment for ages 25–64. Data are not shown for ages younger than 25 years because people younger than age 25 may not have completed their education. Data for those age 65 and older are not shown because reporting quality is poorer at older ages (72). Age-adjusted death rates by educational attainment were computed based on the age-specific rates and the standard population for those ages 25–64. Data were about 97% complete on a state-of-occurrence basis.

### Injury at work

Deaths, crude death rates, and age-adjusted death rates for injury at work (Tables 15 and 16) include those age 15 and older. Information on deaths attributed to injuries at work is derived from a separate item on the death certificate that asks the medical certifier whether the death resulted from an injury sustained at work.

### Infant mortality

IMRs are the most commonly used index for measuring the risk of dying during the first year of life. The rates presented in this report are calculated by dividing the number of infant deaths in a calendar year by the number of live births registered for the same period and are presented as rates per 1,000 or per 100,000 live births. For final birth figures used in the denominator for IMRs, see the report “Births: Final Data for 2022” (61). In contrast to IMRs based on live births, infant death rates are based on the estimated population younger than age 1. Infant death rates that appear in tabulations of age-specific death rates in this report are calculated by dividing the number of infant deaths by the July 1, 2022, population estimate of people younger than age 1. These rates are presented per 100,000 population in this age group. Because of differences in the denominators, infant death rates may differ from IMRs.

There are two sources of infant mortality data: a) the general mortality file, and b) the linked file of live births and infant deaths. Data from the linked file differ from the infant mortality data presented in this report because the linked file includes only those events in which both the birth and the death occur in the United States, and late-filed births. Processing of the linked file allows for further exclusion of infant records due to duplicates and records with additional information that raise questions about an infant’s age. Although the differences are usually very small, IMRs based on the linked file tend to be somewhat smaller than those based on data from the general mortality file as presented in this report. The linked file is the preferred source for infant mortality by race because it uses the mother’s self-reported race from the child’s birth certificate (31), which is more reliable than the infant’s race listed on the death certificate, and because the numerator and denominator are referring to the same person’s race.

### Maternal mortality

Maternal mortality rates are computed based on the number of live births. The maternal mortality rate indicates the likelihood of a pregnant woman dying of maternal causes. The rates are calculated by dividing the number of maternal deaths in a calendar year by the number of live births registered for the same period and are presented as rates per 100,000 live births. Because the population of pregnant women who are at risk of a maternal death is unknown, the number of live births is used as the denominator.

Maternal deaths are defined by WHO as “the death of a woman while pregnant or within 42 days of termination of pregnancy, irrespective of the duration and the site of the pregnancy, from any cause related to or aggravated by the pregnancy or its management but not from accidental or incidental causes” (4). Included in these deaths are ICD–10 codes A34, O00–O95, and O98–O99.

The 2003 revision of the U.S. Standard Certificate of Death introduced a pregnancy-related checkbox question to help identify pregnancy-related deaths. Adopting a pregnancy status question consistent with the standard death certificate increased the identification of maternal deaths. Because maternal mortality was not comparable between states using a pregnancy checkbox and those not using a checkbox, NCHS suspended publishing maternal mortality data after the 2007 data year until all states adopted use of the revised certificate (32).

Beginning in 2018, all 50 states and D.C. used the revised certificate for the entire year including its pregnancy checkbox (in the first part of the 2021 data year, California used a different checkbox from that on the U.S. Standard Certificate of Death that indicates if pregnant within the last year but does not indicate detail on whether pregnant at the time of death, pregnant 42 days before death, or pregnant 2 days to 1 year before death, but California transitioned to use of the standard checkbox later in the 2021 data year.) (32). Because maternal mortality data among states became comparable, NCHS resumed publication of maternal mortality statistics in 2018.

NCHS adopted a method (called the 2018 method) for coding maternal deaths, which was developed to improve the quality of maternal mortality data after studies concluded that implementation of the checkbox had resulted in overreporting of maternal deaths, particularly among older women (32). The 2018 method restricts use of a pregnancy checkbox for identifying maternal deaths to a more limited age group than before. In addition, if the checkbox is the only indication of pregnancy on the death certificate and no other pregnancy information is provided in the cause-of-death section, the 2018 method restricts assignment of maternal codes solely to the underlying cause of death.

Between 2018 and 2020, the 2018 method was implemented manually, but was incorporated into the automated system beginning with the 2021 data year. The transition to automated processing changed the order in which information from the pregnancy checkbox and cause-of-death fields on the death certificate are used to assign ICD–10 underlying cause-of-death codes. As a result, some deaths that would have previously been assigned mostly to O26.8, Other specified pregnancy-related conditions as the underlying cause-of-death code were instead assigned to O98, Maternal infectious and parasitic diseases classifiable elsewhere but complicating pregnancy, childbirth and the puerperium; or O99, Other maternal diseases classifiable elsewhere but complicating pregnancy, childbirth and the puerperium.

### Population bases for computing rates

Populations used for computing death rates and life tables shown in this report represent the population residing in the United States, enumerated as of April 1 for census years before 2020 and estimated as of July 1 for all other years. The populations used for computing death rates for 2022 in Tables B, 1, 2, 6, 8, and 10–12, 15–17, and 22–25 are estimated as of July 1, 2022 based on the Blended Base produced by the U.S. Census Bureau in lieu of the April 1, 2020 decennial population count. The Blended Base consists of the blend of Vintage 2020 population estimates for April 1, 2020 (based on April 1, 2010, decennial census), blended with the 2020 Demographic Analysis Estimates and the 2020 Census Edited File (see https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2022/methods-statement-v2022.pdf). Detailed populations from the 2020 census were not available when this report was prepared. The U.S. Census Bureau provided all population estimates used in this report. When the 2010–2020 intercensal population estimates based on the 2010 and 2020 decennial censuses become available, population-based rates for years 2011–2020 will be recalculated and presented in an upcoming report. Meanwhile, considerable caution should be used in interpreting the rates and trends for the nation and states (73).

Population estimates used to compute death rates for the United States for 2022 are shown for 5-year age groups by Hispanic origin and race in Table V (17).

Table V Estimated population by 5-year age groups, according to Hispanic origin and race, by sex: United States, 2022

[Populations are postcensal estimates based on the Blended Base produced by the U.S. Census Bureau in place of the April 1, 2020, decennial population count. The Blended Base consists of Vintage 2020 Population Estimates for April 1, 2020 (based on the April 1, 2010, decennial census), blended with the 2020 Demographic Analysis Estimates and the 2020 Census Edited File (see: https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2022/methods-statement-v2022.pdf); see Technical Notes in this report]

Hispanic origin and race and sex | All ages | Younger than 1 | Age group
Hispanic origin and race and sex | All ages | Younger than 1 | 1–4 | 5–9 | 10–14 | 15–19 | 20–24 | 25–29 | 30–34 | 35–39
Total^1^ | 333,287,557 | 3,683,113 | 14,855,240 | 20,009,195 | 20,889,839 | 21,635,792 | 22,705,779 | 22,193,164 | 23,308,136 | 22,267,949
Male | 165,283,553 | 1,882,867 | 7,592,228 | 10,231,946 | 10,701,853 | 11,082,043 | 11,601,988 | 11,352,742 | 11,836,820 | 11,302,300
Female | 168,004,004 | 1,800,246 | 7,263,012 | 9,777,249 | 10,187,986 | 10,553,749 | 11,103,791 | 10,840,422 | 11,471,316 | 10,965,649
Hispanic^2^ | 63,664,346 | 998,052 | 3,914,409 | 5,138,033 | 5,425,312 | 5,448,278 | 5,348,842 | 4,890,520 | 4,817,130 | 4,607,877
Male | 32,276,938 | 508,033 | 1,993,334 | 2,617,863 | 2,772,306 | 2,789,251 | 2,736,364 | 2,515,190 | 2,511,946 | 2,428,189
Female | 31,387,408 | 490,019 | 1,921,075 | 2,520,170 | 2,653,006 | 2,659,027 | 2,612,478 | 2,375,330 | 2,305,184 | 2,179,688
Non-Hispanic, single race^3^:
American Indian and Alaska Native | 2,420,972 | 25,196 | 106,731 | 156,510 | 170,252 | 176,542 | 186,474 | 181,475 | 188,952 | 163,408
Male | 1,197,400 | 12,864 | 54,375 | 79,942 | 86,677 | 89,741 | 94,788 | 92,462 | 96,188 | 82,110
Female | 1,223,572 | 12,332 | 52,356 | 76,568 | 83,575 | 86,801 | 91,686 | 89,013 | 92,764 | 81,298
Asian | 20,276,025 | 203,944 | 848,949 | 1,174,461 | 1,119,771 | 1,158,864 | 1,308,563 | 1,480,440 | 1,730,538 | 1,719,043
Male | 9,769,094 | 105,289 | 437,706 | 605,005 | 573,927 | 586,389 | 659,228 | 740,389 | 848,290 | 833,341
Female | 10,506,931 | 98,655 | 411,243 | 569,456 | 545,844 | 572,475 | 649,335 | 740,051 | 882,248 | 885,702
Black | 42,070,471 | 543,753 | 2,113,785 | 2,748,687 | 2,887,521 | 2,930,236 | 3,160,578 | 3,191,592 | 3,369,433 | 2,887,606
Male | 20,226,190 | 275,945 | 1,070,946 | 1,391,158 | 1,467,625 | 1,484,723 | 1,592,836 | 1,610,536 | 1,673,804 | 1,407,022
Female | 21,844,281 | 267,808 | 1,042,839 | 1,357,529 | 1,419,896 | 1,445,513 | 1,567,742 | 1,581,056 | 1,695,629 | 1,480,584
Native Hawaiian or Other Pacific Islander | 635,928 | 8,088 | 33,904 | 45,585 | 43,315 | 44,194 | 44,988 | 46,477 | 53,541 | 52,129
Male | 321,585 | 4,200 | 17,524 | 23,316 | 22,065 | 22,497 | 23,187 | 23,768 | 27,604 | 26,845
Female | 314,343 | 3,888 | 16,380 | 22,269 | 21,250 | 21,697 | 21,801 | 22,709 | 25,937 | 25,284
White | 196,225,966 | 1,707,800 | 7,061,704 | 9,751,038 | 10,285,750 | 11,027,468 | 11,892,505 | 11,764,358 | 12,622,234 | 12,427,017
Male | 97,521,380 | 876,488 | 3,622,083 | 5,005,982 | 5,289,325 | 5,676,512 | 6,108,424 | 6,048,016 | 6,421,573 | 6,328,580
Female | 98,704,586 | 831,312 | 3,439,621 | 4,745,056 | 4,996,425 | 5,350,956 | 5,784,081 | 5,716,342 | 6,200,661 | 6,098,437
Hispanic origin and race and sex | Age group (years)
Hispanic origin and race and sex | 40–44 | 45–49 | 50–54 | 55–59 | 60–64 | 65–69 | 70–74 | 75–79 | 80–84 | 85 and older
Total^1^ | 21,427,416 | 19,624,098 | 20,807,547 | 20,967,014 | 21,118,423 | 18,631,422 | 15,157,017 | 10,861,000 | 6,659,545 | 6,485,868
Male | 10,817,889 | 9,844,989 | 10,434,641 | 10,373,923 | 10,297,980 | 8,873,901 | 7,036,771 | 4,909,686 | 2,825,159 | 2,283,827
Female | 10,609,527 | 9,779,109 | 10,372,906 | 10,593,091 | 10,820,443 | 9,757,521 | 8,120,246 | 5,951,314 | 3,834,386 | 4,202,041
Hispanic^2^ | 4,459,023 | 4,033,387 | 3,640,210 | 3,121,175 | 2,536,929 | 1,908,475 | 1,360,595 | 908,000 | 567,743 | 540,356
Male | 2,324,642 | 2,065,385 | 1,858,866 | 1,573,504 | 1,249,624 | 903,330 | 619,254 | 392,326 | 229,454 | 188,077
Female | 2,134,381 | 1,968,002 | 1,781,344 | 1,547,671 | 1,287,305 | 1,005,145 | 741,341 | 515,674 | 338,289 | 352,279
Non-Hispanic, single race^3^:
American Indian and Alaska Native | 149,913 | 136,358 | 140,876 | 146,519 | 146,327 | 121,996 | 92,365 | 61,210 | 36,815 | 33,053
Male | 74,984 | 67,726 | 69,755 | 70,993 | 69,235 | 56,425 | 42,606 | 27,925 | 16,125 | 12,479
Female | 74,929 | 68,632 | 71,121 | 75,526 | 77,092 | 65,571 | 49,759 | 33,285 | 20,690 | 20,574
Asian | 1,582,521 | 1,471,886 | 1,373,321 | 1,184,527 | 1,064,341 | 937,009 | 755,804 | 502,180 | 325,064 | 334,799
Male | 751,154 | 696,931 | 649,955 | 555,946 | 490,376 | 419,966 | 330,334 | 220,628 | 140,068 | 124,172
Female | 831,367 | 774,955 | 723,366 | 628,581 | 573,965 | 517,043 | 425,470 | 281,552 | 184,996 | 210,627
Black | 2,743,559 | 2,471,784 | 2,568,807 | 2,557,040 | 2,440,524 | 1,995,366 | 1,474,542 | 920,305 | 556,510 | 508,843
Male | 1,315,879 | 1,171,411 | 1,217,767 | 1,197,900 | 1,124,054 | 882,604 | 619,103 | 368,642 | 204,186 | 150,049
Female | 1,427,680 | 1,300,373 | 1,351,040 | 1,359,140 | 1,316,470 | 1,112,762 | 855,439 | 551,663 | 352,324 | 358,794
Native Hawaiian or Other Pacific Islander | 47,053 | 39,300 | 37,172 | 35,371 | 32,492 | 25,874 | 19,635 | 12,708 | 7,251 | 6,851
Male | 24,243 | 20,122 | 18,798 | 17,501 | 16,103 | 12,474 | 9,316 | 6,055 | 3,256 | 2,711
Female | 22,810 | 19,178 | 18,374 | 17,870 | 16,389 | 13,400 | 10,319 | 6,653 | 3,995 | 4,140
White | 12,088,581 | 11,183,313 | 12,781,822 | 13,688,221 | 14,675,149 | 13,461,676 | 11,320,516 | 8,366,001 | 5,111,684 | 5,009,129
Male | 6,157,793 | 5,687,353 | 6,493,318 | 6,847,295 | 7,242,868 | 6,513,923 | 5,354,091 | 3,853,134 | 2,208,276 | 1,786,346
Female | 5,930,788 | 5,495,960 | 6,288,504 | 6,840,926 | 7,432,281 | 6,947,753 | 5,966,425 | 4,512,867 | 2,903,408 | 3,222,783

^1^Includes origin not stated, origin not classifiable, and two or more races reported; see Technical Notes.

^2^Includes people of Hispanic origin of any race; see Technical Notes.

^3^Only one race was reported; see Technical Notes.

SOURCE: National Center for Health Statistics, estimates as of July 1, 2022, U.S. resident population by age, sex, race, and Hispanic origin prepared by U.S. Census Bureau, 2023.

Population estimates used to compute death rates by Hispanic subgroup, marital status, and educational attainment are shown in tables VI, VII, and VIII, respectively. These population estimates were prepared by the U.S. Census Bureau using the 2022, 1-year ACS (74).

Table VI Estimated population and standard error for specified Hispanic origin populations, by 10-year age group and sex: United States, 2022

[Population estimates for Central American, Cuban, Dominican, Mexican, Puerto Rican, South American, and Other and unknown Hispanic populations are based on the 2022 1-year American Community Survey adjusted to postcensal July 1, 2022, resident population control totals; see Technical Notes in this report. Population estimates for Hispanic total (Table V) are based on the Blended Base produced by the U.S. Census Bureau in place of the April 1, 2020, decennial population count. The Blended Base consists of Vintage 2020 Population Estimates for April 1, 2020 (based on April 1, 2010, decennial census), blended with the 2020 Demographic Analysis Estimates and the 2020 Census Edited File (see: https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2022/methods-statement-v2022.pdf). Population estimates by specified Hispanic origin in this table may not add to population estimates for total Hispanic in Table V. Standard errors are shown in parentheses below each population estimate]

Hispanicorigin and sex | Age group
Hispanicorigin and sex | All ages | Younger than 1 | 1–4 | 5–14 | 15–24 | 25–34 | 35–44 | 45–54 | 55–64 | 65–74 | 75–84 | 85 and older
Central American | 6,531,260 | 109,590 | 452,980 | 1,085,720 | 1,109,940 | 1,078,815 | 1,058,105 | 762,780 | 501,485 | 249,525 | 93,210 | 29,110
| (31,775) | (4,115) | (9,267) | (13,765) | (13,256) | (13,013) | (12,523) | (10,092) | (8,193) | (5,538) | (3,484) | (1,910)
Male | 3,357,795 | 53,750 | 230,155 | 550,585 | 583,135 | 563,415 | 581,220 | 403,605 | 245,650 | 105,585 | 32,030 | 8,665
| (23,887) | (3,097) | (7,245) | (10,304) | (10,109) | (9,557) | (9,608) | (7,554) | (6,397) | (3,638) | (2,008) | (1,109)
Female | 3,173,465 | 55,840 | 222,825 | 535,135 | 526,805 | 515,400 | 476,885 | 359,175 | 255,835 | 143,940 | 61,180 | 20,445
| (20,954) | (2,710) | (5,779) | (9,127) | (8,576) | (8,832) | (8,031) | (6,692) | (5,118) | (4,176) | (2,847) | (1,555)
Cuban | 2,435,605 | 23,210 | 116,405 | 263,375 | 269,035 | 348,275 | 334,445 | 336,310 | 333,875 | 208,640 | 134,335 | 67,700
| (18,587) | (2,047) | (4,429) | (6,633) | (6,404) | (7,036) | (7,748) | (6,317) | (6,542) | (4,569) | (4,056) | (2,664)
Male | 1,235,770 | 11,180 | 59,330 | 134,835 | 139,370 | 177,675 | 181,780 | 183,165 | 167,530 | 99,705 | 57,845 | 23,355
| (13,439) | (1,460) | (3,136) | (4,870) | (4,474) | (4,993) | (6,020) | (4,750) | (4,648) | (3,200) | (2,607) | (1,587)
Female | 1,199,835 | 12,030 | 57,075 | 128,540 | 129,665 | 170,600 | 152,665 | 153,145 | 166,345 | 108,935 | 76,490 | 44,345
| (12,840) | (1,434) | (3,128) | (4,504) | (4,581) | (4,957) | (4,877) | (4,164) | (4,604) | (3,261) | (3,107) | (2,140)
Dominican | 2,396,790 | 40,765 | 155,725 | 376,125 | 364,045 | 384,050 | 337,820 | 287,230 | 227,120 | 143,690 | 62,365 | 17,855
| (20,334) | (3,101) | (5,161) | (8,589) | (7,777) | (7,998) | (8,288) | (6,937) | (5,676) | (4,140) | (3,232) | (1,543)
Male | 1,136,300 | 24,250 | 80,380 | 187,345 | 181,860 | 190,725 | 161,590 | 126,175 | 96,295 | 59,490 | 23,120 | 5,070
| (14,649) | (2,668) | (3,724) | (6,048) | (5,862) | (5,866) | (6,073) | (4,916) | (3,854) | (2,713) | (2,095) | (786)
Female | 1,260,490 | 16,515 | 75,345 | 188,780 | 182,185 | 193,325 | 176,230 | 161,055 | 130,825 | 84,200 | 39,245 | 12,785
| (14,102) | (1,581) | (3,573) | (6,099) | (5,111) | (5,436) | (5,641) | (4,894) | (4,167) | (3,127) | (2,461) | (1,327)
Mexican | 37,414,765 | 548,590 | 2,332,280 | 6,594,975 | 6,793,825 | 5,771,985 | 5,271,250 | 4,427,185 | 3,019,135 | 1,705,740 | 717,045 | 232,755
| (61,570) | (9,390) | (14,675) | (27,302) | (22,133) | (23,469) | (26,288) | (20,573) | (18,188) | (12,920) | (8,271) | (4,561)
Male | 19,115,315 | 276,585 | 1,197,190 | 3,368,140 | 3,474,675 | 2,995,475 | 2,759,260 | 2,287,910 | 1,533,660 | 825,580 | 310,560 | 86,280
| (44,026) | (7,426) | (10,649) | (18,691) | (15,842) | (16,741) | (19,010) | (15,385) | (12,934) | (9,336) | (5,352) | (2,824)
Female | 18,299,450 | 272,005 | 1,135,090 | 3,226,835 | 3,319,150 | 2,776,510 | 2,511,990 | 2,139,275 | 1,485,475 | 880,160 | 406,485 | 146,475
| (43,041) | (5,748) | (10,096) | (19,901) | (15,456) | (16,448) | (18,157) | (13,659) | (12,787) | (8,931) | (6,307) | (3,582)
Puerto Rican | 5,905,195 | 86,425 | 365,355 | 963,285 | 899,665 | 869,375 | 816,790 | 698,620 | 595,595 | 365,545 | 182,355 | 62,185
| (29,801) | (3,702) | (8,359) | (13,269) | (10,728) | (11,178) | (11,153) | (10,170) | (8,975) | (6,955) | (4,693) | (3,106)
Male | 2,946,795 | 40,930 | 186,715 | 498,455 | 457,875 | 450,145 | 416,345 | 344,945 | 289,675 | 166,420 | 74,770 | 20,520
| (21,301) | (2,638) | (5,790) | (9,436) | (7,856) | (8,040) | (8,468) | (7,293) | (6,256) | (4,746) | (2,877) | (1,730)
Female | 2,958,400 | 45,495 | 178,640 | 464,830 | 441,790 | 419,230 | 400,445 | 353,675 | 305,920 | 199,125 | 107,585 | 41,665
| (20,841) | (2,596) | (6,028) | (9,328) | (7,306) | (7,766) | (7,258) | (7,088) | (6,435) | (5,084) | (3,708) | (2,580)
South American | 4,667,000 | 57,130 | 235,190 | 608,950 | 622,645 | 694,520 | 739,705 | 680,520 | 532,600 | 306,080 | 139,300 | 50,360
| (26,081) | (3,043) | (6,088) | (10,451) | (9,691) | (10,197) | (10,739) | (9,206) | (8,125) | (6,058) | (4,172) | (2,574)
Male | 2,260,020 | 28,250 | 119,490 | 307,835 | 315,780 | 343,160 | 366,090 | 324,620 | 254,505 | 129,210 | 53,755 | 17,325
| (18,509) | (2,350) | (4,317) | (7,363) | (7,133) | (6,889) | (7,853) | (6,912) | (5,731) | (3,793) | (2,640) | (1,495)
Female | 2,406,980 | 28,880 | 115,700 | 301,115 | 306,865 | 351,360 | 373,615 | 355,900 | 278,095 | 176,870 | 85,545 | 33,035
| (18,376) | (1,933) | (4,292) | (7,417) | (6,560) | (7,518) | (7,325) | (6,081) | (5,760) | (4,723) | (3,230) | (2,096)
Other and unknown Hispanic | 4,203,110 | 65,665 | 261,930 | 667,290 | 712,265 | 567,980 | 537,945 | 456,250 | 432,390 | 299,220 | 147,800 | 54,375
| (24,351) | (3,623) | (6,241) | (10,767) | (9,883) | (8,325) | (9,080) | (8,292) | (7,110) | (6,026) | (3,870) | (2,226)
Male | 2,128,410 | 30,360 | 128,860 | 351,305 | 365,910 | 302,495 | 282,445 | 233,045 | 212,615 | 137,140 | 63,580 | 20,655
| (17,622) | (2,404) | (4,638) | (8,294) | (7,013) | (6,237) | (6,638) | (5,777) | (5,030) | (3,980) | (2,460) | (1,320)
Female | 2,074,700 | 35,305 | 133,070 | 315,985 | 346,355 | 265,485 | 255,500 | 223,205 | 219,775 | 162,080 | 84,220 | 33,720
| (16,807) | (2,710) | (4,176) | (6,866) | (6,964) | (5,514) | (6,196) | (5,949) | (5,025) | (4,525) | (2,988) | (1,792)

SOURCE: Population estimates are based on unpublished tabulations prepared by the U.S. Census Bureau, 2021 1-year American Community Survey.

Table VII Estimated population and standard errors for age 15 and older, by marital status, 10-year age group, and sex: United States, 2022

[Population estimates are based on the 2022 1-year American Community Survey Public Use Microdata Sample adjusted to postcensal July 1, 2022, resident population control totals; see Technical Notes in this report. Standard errors are shown in parentheses below each population estimate]

Marital status and sex | Age group
Marital status and sex | 15 and older | 15–24 | 25–34 | 35–44 | 45–54 | 55–64 | 65–74 | 75 and older
All races | 273,938,835 | 44,231,700 | 45,233,265 | 44,047,640 | 40,476,440 | 42,127,470 | 33,898,080 | 23,924,240
| (145,489) | (41,610) | (60,819) | (68,694) | (53,955) | (60,584) | (50,127) | (43,858)
Never married | 94,079,880 | 41,734,595 | 25,488,645 | 11,657,095 | 6,353,260 | 5,015,260 | 2,681,900 | 1,149,125
| (79,265) | (37,472) | (40,949) | (40,067) | (26,104) | (23,604) | (15,766) | (10,470)
Ever married | 179,858,955 | 2,497,105 | 19,744,620 | 32,390,545 | 34,123,180 | 37,112,210 | 31,216,180 | 22,775,115
| (122,000) | (18,090) | (44,969) | (55,799) | (47,220) | (55,797) | (47,584) | (42,590)
Married | 136,077,390 | 2,371,865 | 18,014,855 | 27,821,515 | 27,202,065 | 27,505,950 | 21,448,070 | 11,713,070
| (100,499) | (17,537) | (42,269) | (49,576) | (37,028) | (45,069) | (36,272) | (28,812)
Widowed | 15,101,235 | 14,655 | 83,925 | 263,660 | 677,595 | 1,986,680 | 4,019,820 | 8,054,900
| (37,495) | (1,558) | (3,597) | (6,008) | (10,108) | (13,896) | (19,499) | (26,056)
Divorced | 28,680,330 | 110,585 | 1,645,840 | 4,305,370 | 6,243,520 | 7,619,580 | 5,748,290 | 3,007,145
| (58,122) | (4,158) | (14,919) | (24,894) | (27,505) | (29,816) | (23,840) | (17,458)
All races, male | 134,830,000 | 22,656,100 | 23,030,350 | 22,262,360 | 20,300,590 | 20,655,950 | 15,948,825 | 9,975,825
| (100,600) | (29,177) | (43,186) | (49,134) | (36,815) | (42,486) | (33,298) | (26,845)
Never married | 50,164,325 | 21,607,010 | 14,061,740 | 6,515,830 | 3,465,545 | 2,732,305 | 1,332,045 | 449,850
| (57,380) | (26,421) | (28,468) | (30,973) | (18,651) | (17,899) | (10,851) | (6,214)
Ever married | 84,665,675 | 1,049,090 | 8,968,610 | 15,746,530 | 16,835,045 | 17,923,645 | 14,616,780 | 9,525,975
| (82,631) | (12,378) | (32,474) | (38,143) | (31,741) | (38,531) | (31,481) | (26,116)
Married | 69,028,525 | 997,910 | 8,250,770 | 13,793,175 | 13,868,535 | 14,032,300 | 11,297,270 | 6,788,565
| (71,216) | (12,065) | (30,701) | (34,519) | (25,802) | (32,183) | (25,695) | (20,744)
Widowed | 3,495,640 | 6,460 | 23,880 | 79,440 | 189,355 | 523,190 | 956,695 | 1,716,620
| (18,517) | (1,074) | (1,753) | (3,687) | (5,189) | (7,783) | (9,101) | (12,440)
Divorced | 12,141,510 | 44,720 | 693,960 | 1,873,915 | 2,777,155 | 3,368,155 | 2,362,815 | 1,020,790
| (37,593) | (2,547) | (10,438) | (15,804) | (17,743) | (19,706) | (15,746) | (9,846)
All races, female | 139,108,835 | 21,575,600 | 22,202,915 | 21,785,280 | 20,175,850 | 21,471,520 | 17,949,255 | 13,948,415
| (105,104) | (29,666) | (42,825) | (48,007) | (39,444) | (43,190) | (37,470) | (34,682)
Never married | 43,915,555 | 20,127,585 | 11,426,905 | 5,141,265 | 2,887,715 | 2,282,955 | 1,349,855 | 699,275
| (54,686) | (26,571) | (29,434) | (25,417) | (18,264) | (15,387) | (11,437) | (8,427)
Ever married | 95,193,280 | 1,448,015 | 10,776,010 | 16,644,015 | 17,288,135 | 19,188,565 | 16,599,400 | 13,249,140
| (89,757) | (13,193) | (31,107) | (40,727) | (34,961) | (40,356) | (35,681) | (33,643)
Married | 67,048,865 | 1,373,955 | 9,764,085 | 14,028,340 | 13,333,530 | 13,473,650 | 10,150,800 | 4,924,505
| (70,911) | (12,727) | (29,054) | (35,584) | (26,558) | (31,551) | (25,601) | (19,996)
Widowed | 11,605,595 | 8,195 | 60,045 | 184,220 | 488,240 | 1,463,490 | 3,063,125 | 6,338,280
| (32,603) | (1,128) | (3,141) | (4,744) | (8,674) | (11,512) | (17,244) | (22,895)
Divorced | 16,538,820 | 65,865 | 951,880 | 2,431,455 | 3,466,365 | 4,251,425 | 3,385,475 | 1,986,355
| (44,328) | (3,286) | (10,659) | (19,233) | (21,017) | (22,375) | (17,900) | (14,416)

SOURCE: Population estimates are based on unpublished tabulations prepared by the U.S. Census Bureau, American Community Survey 2022, 1-Year.

Table VIII Estimated population and standard error for ages 25–64, by educational attainment and sex: United States, 2022

[Population estimates are based on the 2022 1-year American Community Survey adjusted to postcensal July 1, 2022 resident population control totals; see Technical Notes in this report. Standard errors are shown in parentheses below each population estimate]

Education level and sex | Age group
Education level and sex | 25–64 | 25–34 | 35–44 | 45–54 | 55–64
Both sexes | 171,884,815 | 45,233,255 | 44,047,660 | 40,476,435 | 42,127,465
| (140,652) | (78,088) | (74,115) | (65,531) | (62,432)
Less than high school diploma or GED | 16,768,325 | 3,288,105 | 4,334,660 | 4,486,665 | 4,658,895
| (47,116) | (22,135) | (26,188) | (22,744) | (22,953)
High school diploma or GED | 42,722,365 | 10,971,690 | 9,867,025 | 9,770,810 | 12,112,840
| (70,867) | (39,128) | (35,721) | (33,592) | (32,966)
Some college or collegiate degree | 112,394,125 | 30,973,460 | 29,845,975 | 26,218,960 | 25,355,730
| (111,986) | (63,850) | (59,424) | (51,465) | (47,793)
Male | 86,249,250 | 23,030,345 | 22,262,375 | 20,300,590 | 20,655,940
| (99,074) | (53,407) | (53,636) | (46,661) | (43,696)
Less than high school diploma or GED | 9,409,700 | 1,950,865 | 2,479,145 | 2,487,315 | 2,492,375
| (35,871) | (16,480) | (20,224) | (17,126) | (17,687)
High school diploma or GED | 23,822,705 | 6,410,545 | 5,696,735 | 5,415,670 | 6,299,755
| (51,346) | (26,811) | (27,800) | (24,155) | (23,692)
Some college or collegiate degree | 53,016,845 | 14,668,935 | 14,086,495 | 12,397,605 | 11,863,810
| (76,762) | (43,149) | (41,170) | (36,062) | (32,174)
Female | 85,635,565 | 22,202,910 | 21,785,285 | 20,175,845 | 21,471,525
| (99,837) | (56,970) | (51,149) | (46,012) | (44,592)
Less than high school diploma or GED | 7,358,625 | 1,337,240 | 1,855,515 | 1,999,350 | 2,166,520
| (30,549) | (14,778) | (16,638) | (14,967) | (14,629)
High school diploma or GED | 18,899,660 | 4,561,145 | 4,170,290 | 4,355,140 | 5,813,085
| (48,844) | (28,499) | (22,431) | (23,345) | (22,922)
Some college or collegiate degree | 59,377,280 | 16,304,525 | 15,759,480 | 13,821,355 | 13,491,920
| (81,538) | (47,064) | (42,852) | (36,717) | (35,341)

SOURCE: Population estimates are based on unpublished tabulations prepared by the U.S. Census Bureau, American Community Survey, 2022 1-Year.

Populations used for computing death rates by state shown in Table IX are estimated as of July 1, 2022, using the Blended Base (17).

Table IX Estimated population for the United States, each state, Puerto Rico, U.S. Virgin Islands, Guam, American Samoa, and Northern Marianas, 2022

[Populations are postcensal estimates based on the Blended Base produced by the U.S. Census Bureau in place of the April 1, 2020, decennial population count. The Blended Base consists of Vintage 2020 Population Estimates for April 1, 2020 (based on April 1, 2010, decennial census), blended with the 2020 Demographic Analysis Estimates and the 2020 Census Edited File (see: https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2022/methods-statement-v2022.pdf)]

Area | Total | Area | Total
United States | 333,287,557 | New Jersey | 9,261,699
Alabama | 5,074,296 | New Mexico | 2,113,344
Alaska | 733,583 | New York | 19,677,151
Arizona | 7,359,197 | North Carolina | 10,698,973
Arkansas | 3,045,637 | North Dakota | 779,261
California | 39,029,342 | Ohio | 11,756,058
Colorado | 5,839,926 | Oklahoma | 4,019,800
Connecticut | 3,626,205 | Oregon | 4,240,137
Delaware | 1,018,396 | Pennsylvania | 12,972,008
District of Columbia | 671,803 | Rhode Island | 1,093,734
Florida | 22,244,823 | South Carolina | 5,282,634
Georgia | 10,912,876 | South Dakota | 909,824
Hawaii | 1,440,196 | Tennessee | 7,051,339
Idaho | 1,939,033 | Texas | 30,029,572
Illinois | 12,582,032 | Utah | 3,380,800
Indiana | 6,833,037 | Vermont | 647,064
Iowa | 3,200,517 | Virginia | 8,683,619
Kansas | 2,937,150 | Washington | 7,785,786
Kentucky | 4,512,310 | West Virginia | 1,775,156
Louisiana | 4,590,241 | Wisconsin | 5,892,539
Maine | 1,385,340 | Wyoming | 581,381
Maryland | 6,164,660 | Puerto Rico | 3,221,789
Massachusetts | 6,981,974 | U.S. Virgin Islands | 105,413
Michigan | 10,034,113 | Guam | 169,086
Minnesota | 5,717,184 | American Samoa | 45,443
Mississippi | 2,940,057 | Northern Marianas | 51,475
Missouri | 6,177,957
Montana | 1,122,867
Nebraska | 1,967,923
Nevada | 3,177,772
New Hampshire | 1,395,231

SOURCES: U.S. Census Bureau. 2022 population estimates (available from: https://www2.census.gov/programs-surveys/popest/datasets/2020-2022/state/asrh/sc-est2022-alldata6.csv), Puerto Rico 2022 population estimates (available from: https://www2.census.gov/programs-surveys/popest/tables/2020-2022/puerto-rico/asrh/prc-est2022-syasex.xlsx), and international data base, 2022 (available from: https://www.census.gov/data-tools/demo/idb/#/country?YR_ANIM=2022&FIPS_SINGLE=**&dashPages=DASH&COUNTRY_YEAR=2022).

Populations used to compute rates for Puerto Rico, Guam, and Northern Marianas are based on population estimates provided by the U.S. Census Bureau’s International Database (75). Population estimates for each state and territory are not subject to sampling variation because the sources used in demographic analysis are complete counts.

### Computing rates

Except for infant and maternal mortality rates, rates are on an annual basis per 100,000 estimated population residing in the specified area. Infant and maternal mortality rates are per 1,000 or per 100,000 live births. Comparisons made in the text among rates, unless otherwise specified, are statistically significant at the 0.05 level of significance. Lack of comment in this report about any two rates does not mean that the difference was tested and found not to be significant at this level.

Age-adjusted rates (R′ ) are used to compare relative mortality risks among groups and over time. However, they should be viewed as relative indexes rather than as actual measures of mortality risk. They were computed by the direct method—that is, by applying age-specific death rates (R_i_) to the U.S. standard population age distribution (Table X), as in

R^′^ = ∑_i_ (P s i)/(P s) R_i_

where P_si_ is the standard population for age group i and P_s_ is the total U.S. standard population (all ages combined).

Table X U.S. standard population

Age group | Population
All ages | 274,633,642
Younger than 1 | 3,794,901
1–4 | 15,191,619
5–14 | 39,976,619
15–24 | 38,076,743
25–34 | 37,233,437
35–44 | 44,659,185
45–54 | 37,030,152
55–64 | 23,961,506
65–74 | 18,135,514
75–84 | 12,314,793
85 and older | 4,259,173

SOURCE: Anderson RN, Rosenberg HM. Age standardization of death rates:

Implementation of the year 2000 standard. National Vital Statistics Reports; vol 47 no 3.

Hyattsville, MD: National Center for Health Statistics. 1998.

Beginning with the 1999 data year, NCHS adopted a new population standard for use in age-adjusting death rates. Based on the projected year 2000 population of the United States, the new standard replaced the 1940 standard population that had been used for over 50 years. The new population standard affects levels of mortality and, to some extent, trends and group comparisons. Of particular note are the effects on race mortality comparisons. For detailed discussion, see: “Age Standardization of Death Rates: Implementation of the Year 2000 Standard” (76). Beginning with 2003 data, the traditional standard million population along with corresponding standard weights to six decimal places were replaced by the projected year 2000 population age distribution (Table X). The effect of the change is negligible and does not significantly affect comparability with age-adjusted rates calculated using the previous method. All age-adjusted rates shown in this report are based on the 2000 U.S. standard population.

Age-adjusted rates for Puerto Rico, Guam, U.S. Virgin Islands, and Northern Marianas were computed by applying the age-specific death rates to the U.S. standard population. The 2000 standard population used for computing age-adjusted rates for the territories is shown in Table X.

Using the same standard population, death rates for the total population and for each race–sex group were adjusted separately. The age-adjusted rates were based on 10-year age groups. Age-adjusted death rates are not comparable with crude rates.

### Random variation

The mortality data presented in this report are not subject to sampling error. Mortality data, even based on complete counts, may be affected by random variation; that is, the number of deaths that actually occurred may be considered as one of a large series of possible results that could have arisen under the same circumstances (77,78). When the number of deaths is small, perhaps fewer than 100, random variation tends to be relatively large. Therefore, considerable caution must be observed in interpreting statistics based on small numbers of deaths.

Measuring random variability—To quantify the random variation associated with mortality statistics, an assumption must be made regarding the appropriate underlying distribution. Deaths, as infrequent events, can be viewed as deriving from a Poisson probability distribution. The Poisson distribution is simple conceptually and computationally, and provides reasonable, conservative variance estimates for mortality statistics when the probability of dying is relatively low (77). Using the properties of the Poisson distribution, the standard error (SE) associated with the number of deaths (D ) is

SE ( D ) = sqrt(var ( D )) = sqrt(D) [1]

where var(D ) denotes the variance of D.

SE associated with crude and age-specific death rates (R ) assumes that the population denominator (P ) is a constant and is

SE ( R ) = sqrt(var ((D)/(P^2^))) = sqrt((1)/(P^2^) var ( D )) = sqrt((D)/(P^2^)) = (R)/(sqrt(D)) [2]

The coefficient of variation or relative standard error (RSE) is a useful measure of relative variation. RSE is calculated by dividing the statistic (such as number of deaths or death rate) into its SE and multiplying by 100. For the number of deaths,

RSE ( D ) = 100 (SE ( D ))/(D) = 100 (sqrt(D))/(D) = 100 sqrt((1)/(D))

For crude and age-specific death rates,

RSE ( R ) = 100 (SE ( R ))/(R) = 100 (R / sqrt(D))/(R) = 100 sqrt((1)/(D))

Thus,

RSE ( D ) = RSE ( R ) = 100 sqrt((1)/(D)) [3]

SE of the age-adjusted death rate (R′ ) is

SE ( R^′^ ) = sqrt(∑_i_ ((P_s_ i)/(P_s_))^2^ var ( R_i_ )) = sqrt(∑_i_ ((P_s_ i)/(P_s_))^2^ ((R_i_^2^)/(D_i_))) [4]

where:

- R_i_ is the age-specific rate for the i th age group.
- P_si_ is the age-specific standard population for the i th age group from the U.S. standard population age distribution (see Table X and Age-adjusted death rate in the “Definition of terms”).
- P_s_ is the total U.S. standard population (all ages combined).
- D_i_ is the number of deaths for the i th age group.

RSE for the age-adjusted rate, RSE(R′), is calculated by dividing SE(R′ ) from Formula 4 by the age-adjusted death rate, R′ , and multiplying by 100, as in

RSE ( R^′^ ) = 100 (SE ( R^′^ ))/(R^′^)

For tables showing infant and maternal mortality rates based on live births (B ) in the denominator, calculation of SE assumes random variability in both the numerator and denominator. SE for IMR is:

SE ( I M R ) = I M R · sqrt((var ( D ))/(E ( D )^2^) + (var ( B ))/(E ( B )^2^)) = I M R · sqrt((1)/(D) + (1)/(B)) [5]

where the number of births, B, is also assumed to be distributed according to a Poisson distribution, and E(B ) is the expectation of B.

RSE for IMR is

RSE ( I M R ) = 100 (SE ( I M R ))/(I M R) = 100 sqrt((1)/(D) + (1)/(B)) [6]

For maternal mortality rates, Formulas 5 and 6 may be used, substituting the maternal mortality rate for IMR.

Formulas 1–6 may be used for all tables presented in this report except for death rates and age-adjusted death rates shown in Tables 3, 13, and 14, which are calculated using population figures that are subject to sampling error, and for rates adjusted for misclassification in Table VI.

SE associated with the age-specific death rates adjusted for Hispanic origin and race misclassification ( R^,^_i_ ) on death certificates assumes the population denominator (P_i_) is a constant and is

S E ( R^,^_i_ ) = sqrt([ ( C R_i_^2^ S E ( D_i_ )^2^ ) + ( D_i_^2^ S E ( C R_i_ )^2^ ) ] / P_i_^2^) [7]

SE of the age-adjusted death rate adjusted for Hispanic origin and race misclassification ( R^'^^,^ ) is

S E ( R^'^^,^ ) = sqrt(∑ i ((P_s i_)/(P_s_))^2^ S E ( R^'^^,^ )^2^) [8]

Again, this is a major issue. Classification quality has been evaluated for both race and a combination of Hispanic origin and race. So, there are ratios for “White” regardless of Hispanic origin and for “White non-Hispanic” where:

- R^,^_i_ is the age-specific rate adjusted for Hispanic origin and race misclassification on death certificates for the i th age group.
- P_i_ is the age-specific population for the i th age group.
- D_i_ is the age-specific number of deaths for the i th age group.
- CR_i_ is the age-specific classification ratio for the i th age group (see Table V).
- P_si_ is the age-specific standard population for the i th age group from the U.S. standard age distribution (see Table X).
- P_s_ is the total U.S. standard population (all ages combined).

Suppression of unreliable rates—Beginning with 1989 data, an asterisk is shown in place of a crude or age-specific death rate based on fewer than 20 deaths, the equivalent of an RSE of 23% or more. The limit of 20 deaths is a convenient, if somewhat arbitrary, benchmark, below which rates are considered to be too statistically unreliable for presentation. For infant and maternal mortality rates, the same threshold of fewer than 20 deaths is used to determine whether an asterisk is presented in place of the rate. For age-adjusted death rates, the suppression criterion is based on the sum of age-specific deaths; that is, if the sum of the age-specific deaths is less than 20, an asterisk replaces the rate.

Tables 3, 13, and 14—Rates for Central American, Cuban, Dominican, Mexican, Puerto Rican, South American, and Other Hispanic populations in Table 3, by marital status in Table 13, and by educational attainment in Table 14 are based on population estimates derived from 1-year ACS Public Use Microdata Sample for 2022 and adjusted to resident population control totals (74). As a result, the rates are subject to sampling variability in the denominator as well as random variability in the numerator.

For crude and age-specific death rates (R ), the SE is calculated as

SE (R) = R · sqrt((1)/(D) + ((SE (P))/(P))^2^) [9]

For age-adjusted death rates (R′ )

SE ( R^′^ ) = sqrt(∑_i_ ((P_s_ i)/(P_s_))^2^ · R_i_^2^ [(1)/(D_i_) + ((SE ( P_i_ ))/(P_i_))^2^]) [10]

where SE(P ) in Formulas 9 and 10 represents the SEs of ACS population estimates. SEs of ACS population estimates used in this report are presented in Table VI by Central American, Cuban, Dominican, Mexican, Puerto Rican, South American, and Other Hispanic populations; in Table VII by marital status; and in Table VIII by educational attainment.

In Tables 3, 13, and 14, sampling variability in the population denominator had a substantial impact on the overall variability in the death rate. Therefore, the number of deaths in the numerator was not used as the sole suppression factor. RSEs for rates shown in Tables 3, 13, and 14 are derived from Formulas 9 and 10 by dividing the result of Formula 9 by the crude and age-specific rate, and the result of Formula 10 by the age-adjusted rate, and then multiplying by 100. Rates are replaced by asterisks if the calculated RSE is 23% or more.

Confidence intervals and statistical tests based on 100 deaths or more—When the number of deaths is large, a normal approximation may be used in calculating confidence intervals and statistical tests. How large, in terms of number of deaths, is to some extent subjective. In general, for crude and age-specific death rates and for infant and maternal mortality rates, the normal approximation performs well when the number of deaths is 100 or more. For age-adjusted rates, the criterion for use of the normal approximation is somewhat more complicated (78,79). Formula 11 is used to calculate 95% confidence limits for the death rate when the normal approximation is appropriate:

L(R ) = R – 1.96 (SE(R )) [11]

and

L(R ) = R – 1.96 (SE(R ))

where L(R ) and U(R ) are the lower and upper limits of the confidence interval, respectively. The resulting 95% confidence interval can be interpreted to mean that the chances are 95 in 100 that the “true” death rate falls between L(R ) and U(R ). For example, suppose that the crude death rate for Malignant neoplasms is 186.0 per 100,000 population based on 565,469 deaths. Lower and upper 95% confidence limits using Formula 11 are calculated as

L(186.0) = 186.0 – 1.96 (0.25) = 185.5

and

U(186.0) = 186.0 + 1.96 (0.25) = 186.5

Thus, the chances are 95 in 100 that the true death rate for Malignant neoplasms is between 185.5 and 186.5. Formula 11 can also be used to calculate 95% confidence intervals for the number of deaths, age-adjusted death rates, IMRs, and other mortality statistics when the normal approximation is appropriate by replacing R with D, R′, IMR, or others.

When testing the difference between two rates, R_1_ and R_2_ (each based on 100 or more deaths), the normal approximation may be used to calculate a test statistic, z, such that

z = (R_1_ ​ − ​ R_2_)/(sqrt(SE ( R_1_ )^2^ + SE ( R_2_ )^2^)) [12]

If | z | ≥ 1.96, then the difference between the rates is statistically significant at the 0.05 level. If | z | < 1.96, then the difference is not statistically significant. Formula 12 can also be used to perform tests for other mortality statistics when the normal approximation is appropriate (when both statistics being compared meet the normal criteria) by replacing R_1_ and R_2_ with D_1_ and D_2_, R_1_^'^ and R_2_^'^ , or others. For example, suppose that the male age-adjusted death rate for Malignant neoplasms of trachea, bronchus and lung (lung cancer) is 65.1 per 100,000 U.S. standard population in the previous data year (R_1_) and per 100,000 U.S. standard population in the current data year (R_2_). SE for each of these figures, SE(R_1_) and SE(R_2_), is calculated using Formula 4. A test using Formula 12 can determine if the decrease in the age-adjusted rate is statistically significant:

z = (65.1 − 63.6)/(sqrt(( 0.222 )^2^ + ( 0.217 )^2^)) = 4.83

Because z = 4.83 > 1.96, the decrease from the previous data year to the current data year in the male age-adjusted death rate for lung cancer is statistically significant.

Confidence intervals and statistical tests based on fewer than 100 deaths—When the number of deaths is not large (fewer than 100), the Poisson distribution cannot be approximated by the normal distribution. The normal distribution is symmetrical, with a range from – ∞ to + ∞. As a result, confidence intervals based on the normal distribution also have this range. The number of deaths or the death rate, however, cannot be less than zero. When the number of deaths is very small, approximating confidence intervals for deaths and death rates using the normal distribution will sometimes produce lower confidence limits that are negative. The Poisson distribution, in contrast, is an asymmetric distribution with zero as a lower bound—confidence limits based on this distribution will never be less than zero. A simple method based on the more general family of gamma distributions, of which the Poisson is a member, can be used to approximate confidence intervals for deaths and death rates when the number of deaths is small (76,78). For more information regarding how the gamma method is derived, see “Derivation of gamma method” at the end of this section.

Calculations using the gamma method can be made using commonly available spreadsheet programs or statistical software (such as Excel or SAS) that include an inverse gamma function. In Excel, the function “gammainv (probability, alpha, beta)” returns values associated with the inverse gamma function for a given probability between zero and one. For 95% confidence limits, the probability associated with the lower limit is 0.05/2 = 0.025, and with the upper limit, 1 – (0.05/2) = 0.975. Alpha and beta are parameters associated with the gamma distribution. For the number of deaths and crude and age-specific death rates, alpha = D (the number of deaths) and beta = 1. In Excel, the following formulas can be used to calculate lower and upper 95% confidence limits for the number of deaths and crude and age-specific death rates:

L(D ) = GAMMAINV(0.025, D, 1)

and

U(D ) = GAMMAINV(0.975, D + 1, 1)

Confidence limits for the death rate are then calculated by dividing L(D ) and U(D ) by the population (P ) at risk of dying (see Formula 19).

Alternatively, 95% confidence limits can be estimated using the lower and upper confidence limit factors shown in Table XI. For the number of deaths, D, and the death rate, R,

L(D ) = L • D and U(D ) = U • D [13]

and

L(R ) = L • R and U(R ) = U • R [14]

where L and U in both formulas are the lower and upper confidence limit factors that correspond to the appropriate number of deaths, D, in Table XI. For example, suppose that the death rate for American Indian and Alaska Native non-Hispanic females ages 1–4 is 39.5 per 100,000 and based on 50 deaths. Applying Formula 14, values for L and U from Table XI for 50 deaths are multiplied by the death rate, 39.5, such that

L(R ) = L(39.5) = 0.742219 • 39.5 = 29.3

and

U(R ) = U(39.5) = 1.318375 • 39.5 = 52.1

Table XI Lower and upper 95% confidence limit factors for the number of deaths and death rate when the number of deaths is less than 100

Number of deaths (D ) | Lower confidence limit (L ) | Upper confidence limit (U ) | Number of deaths (D ) | Lower confidence limit (L ) | Upper confidence limit (U )
1 | 0.025318 | 5.571643 | 51 | 0.744566 | 1.314815
2 | 0.121105 | 3.612344 | 52 | 0.746848 | 1.311367
3 | 0.206224 | 2.922424 | 53 | 0.749069 | 1.308025
4 | 0.272466 | 2.560397 | 54 | 0.751231 | 1.304783
5 | 0.324697 | 2.333666 | 55 | 0.753337 | 1.301637
6 | 0.366982 | 2.176579 | 56 | 0.755389 | 1.298583
7 | 0.402052 | 2.060382 | 57 | 0.757390 | 1.295616
8 | 0.431729 | 1.970399 | 58 | 0.759342 | 1.292732
9 | 0.457264 | 1.898311 | 59 | 0.761246 | 1.289927
10 | 0.479539 | 1.839036 | 60 | 0.763105 | 1.287198
11 | 0.499196 | 1.789276 | 61 | 0.764921 | 1.284542
12 | 0.516715 | 1.746799 | 62 | 0.766694 | 1.281955
13 | 0.532458 | 1.710030 | 63 | 0.768427 | 1.279434
14 | 0.546709 | 1.677830 | 64 | 0.770122 | 1.276978
15 | 0.559692 | 1.649348 | 65 | 0.771779 | 1.274582
16 | 0.571586 | 1.623937 | 66 | 0.773400 | 1.272245
17 | 0.582537 | 1.601097 | 67 | 0.774986 | 1.269965
18 | 0.592663 | 1.580431 | 68 | 0.776539 | 1.267738
19 | 0.602065 | 1.561624 | 69 | 0.778060 | 1.265564
20 | 0.610826 | 1.544419 | 70 | 0.779549 | 1.263440
21 | 0.619016 | 1.528606 | 71 | 0.781008 | 1.261364
22 | 0.626695 | 1.514012 | 72 | 0.782438 | 1.259335
23 | 0.633914 | 1.500491 | 73 | 0.783840 | 1.257350
24 | 0.640719 | 1.487921 | 74 | 0.785215 | 1.255408
25 | 0.647147 | 1.476197 | 75 | 0.786563 | 1.253509
26 | 0.653233 | 1.465232 | 76 | 0.787886 | 1.251649
27 | 0.659006 | 1.454947 | 77 | 0.789184 | 1.249828
28 | 0.664493 | 1.445278 | 78 | 0.790459 | 1.248045
29 | 0.669716 | 1.436167 | 79 | 0.791709 | 1.246298
30 | 0.674696 | 1.427562 | 80 | 0.792938 | 1.244587
31 | 0.679451 | 1.419420 | 81 | 0.794144 | 1.242909
32 | 0.683999 | 1.411702 | 82 | 0.795330 | 1.241264
33 | 0.688354 | 1.404372 | 83 | 0.796494 | 1.239650
34 | 0.692529 | 1.397400 | 84 | 0.797639 | 1.238068
35 | 0.696537 | 1.390758 | 85 | 0.798764 | 1.236515
36 | 0.700388 | 1.384422 | 86 | 0.799871 | 1.234992
37 | 0.704092 | 1.378368 | 87 | 0.800959 | 1.233496
38 | 0.707660 | 1.372578 | 88 | 0.802029 | 1.232028
39 | 0.711098 | 1.367033 | 89 | 0.803082 | 1.230586
40 | 0.714415 | 1.361716 | 90 | 0.804118 | 1.229170
41 | 0.717617 | 1.356613 | 91 | 0.805138 | 1.227778
42 | 0.720712 | 1.351709 | 92 | 0.806141 | 1.226411
43 | 0.723705 | 1.346993 | 93 | 0.807129 | 1.225068
44 | 0.726602 | 1.342453 | 94 | 0.808102 | 1.223747
45 | 0.729407 | 1.338079 | 95 | 0.809060 | 1.222448
46 | 0.732126 | 1.333860 | 96 | 0.810003 | 1.221171
47 | 0.734762 | 1.329788 | 97 | 0.810933 | 1.219915
48 | 0.737321 | 1.325855 | 98 | 0.811848 | 1.218680
49 | 0.739806 | 1.322053 | 99 | 0.812751 | 1.217464
50 | 0.742219 | 1.318375

SOURCE: Anderson RN, Rosenberg HM. Age standardization of death rates: Implementation of the year 2000 standard. National Vital Statistics Reports; vol 47 no. 3. Hyattsville, MD: National Center for Health Statistics. 1998.

These confidence limits indicate that the chances are 95 in 100 that the actual death rate for American Indian and Alaska Native non-Hispanic females ages 1–4 is between 29.3 and 52.1 per 100,000.

Although the calculations are similar, confidence intervals based on small numbers for age-adjusted death rates, infant and maternal mortality rates, and rates that are subject to sampling variability in the denominator are somewhat more complicated (78).

Refer to the last published version of the Mortality Technical Appendix for more details: https://www.cdc.gov/nchs/data/statab/techap95.pdf (79).

When comparing the difference between two rates (R_1_ and R_2_), where one or both of the rates are based on fewer than 100 deaths, a comparison of 95% confidence intervals may be used as a statistical test. If the 95% confidence intervals do not overlap, then the difference can be said to be statistically significant at the 0.05 level. A simple rule of thumb is: If R_1_ > R_2_, then test if L(R_1_) > U(R_2_), or if R_2_ > R_1_, then test if L(R_2_) > U(R_1_). Positive tests denote statistical significance at the 0.05 level. For example, suppose that American Indian and Alaska Native non-Hispanic females ages 1–4 have a death rate (R_1_) of 39.5 based on 50 deaths, and Asian females ages 1–4 have a death rate (R_2_) of 20.1 per 100,000 based on 86 deaths. The 95% confidence limits for R_1_ and R_2_ calculated using Formula 14 would be

L(R_1_) = L(39.5) = 0.742219 • 39.5 = 29.3

and

U(R_1_) = U(39.5) = 1.318375 • 39.5 = 52.1

L(R_2_) = L(20.1) = 0.799871 • 20.1 = 16.1

and

U(R_2_) = U(20.1) = 1.234992 • 20.1 = 24.8

Because R_1_ > R_2_ and L(R_1_) > U(R_2_), it can be concluded that the difference between the death rates for American Indian and Alaska Native females ages 1–4 and Asian females of the same age is statistically significant at the 0.05 level. That is, accounting for random variability, Asian females ages 1–4 have a death rate significantly lower than that for American Indian and Alaska Native females of the same age.

This test may also be used to perform tests for other statistics when the normal approximation is not appropriate for one or both of the statistics being compared, by replacing R_1 _and R_2_ with D_1_ and D_2_, R_1_^'^ and R_2_^'^ , or others.

Users of the method of comparing confidence intervals should be aware that this method is a conservative test for statistical significance—the difference between two rates may, in fact, be statistically significant even though confidence intervals for the two rates overlap (80). Caution should be observed when interpreting a nonsignificant difference between two rates, especially when the lower and upper limits being compared overlap only slightly.

Derivation of gamma method—For a random variable X that follows a gamma distribution Γ(y,z ), where y and z are the parameters that determine the shape of the distribution (80), E(X) = yz and Var(X) = yz ^2^. For the number of deaths, D, E(D) = D and Var(D) = D. It follows that y = D and z = 1, and thus,

D ~ Γ(D,1) [15]

From Equation 13, it is clear that the shape of the distribution of deaths depends only on the number of deaths.

For the death rate, R, E(R ) = R and Var(R ) = D/P ^2^. It follows, in this case, that y = D and z = P ^–1^, and thus,

R ~ Γ(D,P ^–1^) [16]

A useful property of the gamma distribution is that for X ~ Γ(y,z), X can be divided by z such that X/z~ Γ(y,1). This converts the gamma distribution into a simplified, standard form, dependent only on parameter y. Expressing Equation 14 in its simplified form gives:

R/P ^–1^ = D ~ Γ(D,1) [17]

From Equation 15, it is clear that the shape of the distribution of the death rate is also dependent solely on the number of deaths.

Using the results of Equations 13 and 15, the inverse gamma distribution can be used to calculate upper and lower confidence limits. Lower and upper 100(1 – α) percentage confidence limits for the number of deaths, L(D ) and U(D ), are estimated as

L(D ) = Γ^–1^_(D,1)_(α / 2) and U(D ) = Γ^–1^_(D+1,1)_(1 – α / 2) [18]

where Γ^–1^ represents the inverse of the gamma distribution and D + 1 in the formula for U(D ) reflects a continuity correction, which is necessary because D is a discrete random variable and the gamma distribution is a continuous distribution. For a 95% confidence interval, α = 0.05. For the death rate, it can be shown that

L(R ) = L(D )/P and U(R ) = U(D )/P [19]

For more detail regarding the derivation of the gamma method and its application to age-adjusted death rates and other mortality statistics, see References (14,77,81).

### Availability of mortality data

Mortality data are available in publications, unpublished tables, and electronic products as described on the NCHS mortality website: https://www.cdc.gov/nchs/deaths.htm. More detailed analysis than this report provides can be obtained from the mortality public-use data set issued each data year. Since 1968, the data set has been available through NCHS in ASCII format and can now be downloaded: https://www.cdc.gov/nchs/data_access/Vitalstatsonline.htm. Additional resources available from NCHS include Vital Statistics of the United States, Mortality; Vital and Health Statistics, Series 20 reports; and National Vital Statistics Reports.

### Definition of terms

Age-adjusted death rate—The death rate used to make comparisons of relative mortality risks across groups and over time. This rate should be viewed as a construct or an index rather than a direct or actual measure of mortality risk. Statistically, it is a weighted average of age-specific death rates, where the weights represent the fixed population proportions by age.

Age-specific death rate—Deaths per 100,000 population in a specified age group, such as 1–4 or 5–9 years, for a specified period.

Crude death rate—Total deaths per 100,000 population for a specified period. This rate represents the average chance of dying during a specified period for people in the entire population.

Infant deaths—Deaths of infants younger than age 1 year.

Neonatal deaths—Deaths of infants ages 0–27 days.

Postneonatal deaths—Deaths of infants ages 28 days–11 months.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/.

For questions or general information about NCHS: Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info