# Volume 73 Number 5 Infant Mortality in the United States, 2022: Data From the Period Linked Birth/Infant Death File

### Objectives

This report presents final 2022 infant mortality statistics by age at death, maternal race and Hispanic origin, maternal age, gestational age, leading causes of death, and maternal state of residence. Trends in infant mortality are also examined.

### Methods

Descriptive tabulations of data are presented and interpreted for infant deaths and infant mortality rates using the 2022 period linked birth/infant death file. The linked birth/infant death file is based on birth and death certificates registered in all 50 states and the District of Columbia.

### Results

A total of 20,577 infant deaths were reported in the United States in 2022, up 3% from 2021. The U.S. infant mortality rate was 5.61 infant deaths per 1,000 live births, a 3% increase from the rate of 5.44 in 2021. The neonatal mortality rate increased 3% from 3.49 in 2021 to 3.59 in 2022, and the postneonatal mortality rate increased 4% from 1.95 to 2.02. The overall infant mortality rate increased for infants of American Indian and Alaska Native non-Hispanic, White non-Hispanic, and Dominican women in 2022 compared with 2021; changes in rates for the other race and Hispanic-origin groups were not significant. Infants of Black non-Hispanic women had the highest mortality rate (10.90) in 2022, followed by infants of American Indian and Alaska Native non-Hispanic and Native Hawaiian or Other Pacific Islander non-Hispanic (9.06 and 8.50, respectively), Hispanic (4.89), White non-Hispanic (4.52), and Asian non-Hispanic (3.51) women. Mortality rates increased from 2021 to 2022 among preterm (less than 37 weeks of gestation) infants (33.59 to 34.78) and for infants born term (37 to 41 weeks of gestation) (2.08 to 2.18). The five leading causes of infant death in 2022 were the same as in 2021. Infant mortality rates by state for 2022 ranged from a low of 3.32 in Massachusetts to a high of 9.11 in Mississippi.

## Report erratum

This report was revised on August 22, 2024, to correct for errors in imputed birthweight values affecting 0.37% of records. The number of deaths and infant mortality rates by birthweight category have been revised; see Table 2.

## Introduction

This report presents infant mortality statistics based on data from the 2022 period linked birth/infant death file. Infant mortality and mortality rates are described by age at death, maternal race and Hispanic origin, maternal age, gestational age, leading causes of death, and maternal state of residence. Infant mortality trends are also presented by selected characteristics. In the linked file, information from the death certificate is linked to information from the birth certificate for each infant younger than age 1 year who died in the 50 states, the District of Columbia, Puerto Rico, or Guam during 2022 (1). The purpose of the linkage is to use variables available from the birth certificate to conduct more detailed analyses of infant mortality patterns (2,3). The linked birth/infant death data set also is the preferred source for examining infant mortality by race and Hispanic origin. Infant mortality rates by race and Hispanic origin, based on maternal race and Hispanic origin, are more accurately measured from the birth certificate compared with the death certificate.

For 2022, linked birth/infant death data are not available for American Samoa, Commonwealth of the Northern Marianas, and U.S. Virgin Islands. Some rates calculated from the mortality file differ from those published using the linked file. More details can be found elsewhere (1).

## Methods

Data shown in this report are based on birth and infant death certificates registered in all states, the District of Columbia, Puerto Rico, and Guam. As part of the Vital Statistics Cooperative Program, each state provides matching birth and death certificate numbers for each infant younger than age 1 year who died during 2022 to the National Center for Health Statistics. Further discussion of the process of linking births and deaths occurring in different states and file production can be found in the Methodology section of the “User Guide to the 2022 Period/2021 Cohort Linked Birth/Infant Death Public Use File” (1).

The period linked file for 2017 marked the first data year for which the linked birth data for infant deaths for all 50 states and the District of Columbia were based on the 2003 revision of the U.S. Standard Certificate of Live Birth (4) and, accordingly, the first year for which national data on race and Hispanic-origin categories based on 1997 Office of Management and Budget standards became available (5).

In 2022, 98.6% of all infant death records were successfully linked to their corresponding birth records. These records were weighted to adjust for the 1.4% of infant death records that were not linked to their corresponding birth certificates (1) (Technical Notes).

Information for age and race of mother is imputed if it is not reported on the birth certificate. In 2022, race of mother was imputed for 7.6% of births; mother’s age was imputed for 0.01% of births (2,3).

All race and Hispanic-origin data are based on single-race reporting and are consistent with the 1997 Office of Management and Budget standards and differ from the bridged-race categories shown in previous reports (5). Maternal race and Hispanic-origin categories presented are American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native), Asian non-Hispanic (subsequently, Asian), Black non-Hispanic (subsequently, Black), Native Hawaiian or Other Pacific Islander non-Hispanic (subsequently, Native Hawaiian or Other Pacific Islander), White non-Hispanic (subsequently, White), and Hispanic. Race and Hispanic origin are reported separately on the birth certificate. Data are shown in most cases for five specified Hispanic groups: Central and South American, Cuban, Dominican, Mexican, and Puerto Rican. Additional details on Hispanic origin are available elsewhere (3). Comparisons between 2022 and 2021 by race and Hispanic origin are made in this report. The 2003 revision of the U.S. Standard Certificate of Live Birth allows the reporting of five race categories for each parent (6)—either alone, as in single race, or in combination, as in more than one race or multiple races—in accordance with the 1997 revised Office of Management and Budget standards (5). Further details on race reporting are available elsewhere (3).

Cause-of-death statistics are classified in accordance with the International Statistical Classification of Diseases and Related Health Problems, 10th Revision (ICD–10) (7) (Technical Notes).

### Data by maternal and infant characteristics

This report presents descriptive tabulations of infant mortality data by a variety of maternal and infant characteristics. These tabulations are useful for understanding the basic relationships between risk factors and infant mortality, unadjusted for the possible effects of other variables. However, women with one risk factor often have other risk factors. For example, teen mothers are more likely to be unmarried and of a low-income status, while mothers who do not receive prenatal care are more likely to be of a low-income status and uninsured. The preferred method for disentangling the multiple interrelationships among risk factors is multivariate analysis; however, an understanding of the basic relationships between risk factors and infant mortality is the first step before more sophisticated types of analyses and may help identify high-risk subgroups for prevention efforts. This report presents several key risk factors for infant mortality: age at death, maternal race and Hispanic origin, maternal age, gestational age, leading causes of infant death, and maternal state of residence. For brevity, additional selected risk factors (sex, birthweight, plurality, and nativity [mother’s place of birth]) are presented in tables but not discussed in this report.

Race and Hispanic origin—Infant mortality rates are presented by race and Hispanic origin of the mother. The linked file is useful for computing accurate infant mortality rates by these characteristics because the race and Hispanic origin of the mother from the birth certificate are used in both the numerator and denominator of the infant mortality rate. In contrast, for rates based on the vital statistics mortality file, race information for the denominator is the race of the mother as reported on the birth certificate, while race information for the numerator is the race of the decedent as reported on the death certificate (2,3,8). More detail on the reliability of race and Hispanic-origin data from the linked file compared with the mortality file is available elsewhere (8).

Statistical significance—Statements in the text have been tested for statistical significance, and a statement that a given infant mortality rate is higher or lower than another rate indicates that the rates are significantly different using a two-tailed z test at the alpha level of 0.05. Comparisons between state rates and the U.S. rate take into account each state’s contribution to the U.S. rate. As a result, each state rate is compared with a unique U.S. rate independent of the state’s contribution to the total U.S. rate. Information on the methods used to test for statistical significance, as well as information on differences between period and cohort data, the weighting of the linked file, maternal age, period of gestation, birthweight, and cause-of-death classification is also available (1) (Technical Notes).

## Results

### Trends in infant mortality and infant age at death

- In 2022, 20,577 infant deaths were reported in the United States, an increase of 3% from 2021 (19,928) (Figure 1, Table 1). The infant mortality rate was 5.61 deaths per 1,000 live births in 2022, an increase of 3% from the 2021 rate of 5.44.
- The U.S. infant mortality rate has generally trended downward since 1995 (the first year that the period linked birth/infant death file was available) and in 2022 was down 19% since the last increase in 2002 (6.95).
- The 2022 neonatal mortality rate (infant deaths at less than 28 days) of 3.59 was 3% higher than the rate in 2021 (3.49). The neonatal mortality rate has generally declined since 1995 and decreased 23% since the last increase in 2002 (4.67).
- The 2022 postneonatal mortality rate (infant deaths at 28 days or more) increased 4% to 2.02 from 1.95 in 2021. The postneonatal mortality rate has also generally declined since 1995 and decreased 11% since 2002 (2.28).

Figure 1 Infant, neonatal, and postneonatal mortality rates: United States, 1995–2022

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 1 is a line graph showing infant, neonatal and postneonatal mortality rates from 1995 through 2022.

Table 1

Live births; infant, neonatal, and postneonatal deaths; and mortality rate: United States, 1995–2022, and by maternal race and Hispanic origin, 2017–2022

Race and Hispanic origin and year | Number | | | | Deaths per 1,000 live births
Race and Hispanic origin and year | Live births | Infant deaths | Neonatal deaths | Postneonatal deaths | Infant | Neonatal | Postneonatal
All race and Hispanic-origin groups
2022 | 3,667,758 | 20,577 | 13,158 | 7,419 | 5.61 | 3.59 | 2.02
2021 | 3,664,292 | 19,928 | 12,797 | 7,131 | 5.44 | 3.49 | 1.95
2020 | 3,613,647 | 19,578 | 12,866 | 6,712 | 5.42 | 3.56 | 1.86
2019 | 3,747,540 | 20,927 | 13,834 | 7,093 | 5.58 | 3.69 | 1.89
2018 | 3,791,712 | 21,498 | 14,329 | 7,169 | 5.67 | 3.78 | 1.89
2017 | 3,855,500 | 22,341 | 14,844 | 7,497 | 5.79 | 3.85 | 1.94
2016 | 3,945,875 | 23,157 | 15,303 | 7,854 | 5.87 | 3.88 | 1.99
2015 | 3,978,497 | 23,458 | 15,672 | 7,786 | 5.90 | 3.94 | 1.96
2014 | 3,988,076 | 23,211 | 15,737 | 7,474 | 5.82 | 3.95 | 1.87
2013 | 3,932,181 | 23,446 | 15,893 | 7,553 | 5.96 | 4.04 | 1.92
2012 | 3,952,841 | 23,654 | 15,887 | 7,767 | 5.98 | 4.02 | 1.96
2011 | 3,953,590 | 24,001 | 16,065 | 7,936 | 6.07 | 4.06 | 2.01
2010 | 3,999,386 | 24,572 | 16,193 | 8,379 | 6.14 | 4.05 | 2.10
2009 | 4,130,665 | 26,408 | 17,261 | 9,148 | 6.39 | 4.18 | 2.21
2008 | 4,247,726 | 28,075 | 18,238 | 9,837 | 6.61 | 4.29 | 2.32
2007 | 4,316,233 | 29,153 | 19,094 | 10,059 | 6.75 | 4.42 | 2.33
2006 | 4,265,593 | 28,509 | 19,041 | 9,468 | 6.68 | 4.46 | 2.22
2005 | 4,138,573 | 28,384 | 18,782 | 9,602 | 6.86 | 4.54 | 2.32
2004 | 4,112,055 | 27,860 | 18,602 | 9,258 | 6.78 | 4.52 | 2.25
2003 | 4,090,007 | 27,995 | 18,935 | 9,060 | 6.84 | 4.63 | 2.22
2002 | 4,021,825 | 27,970 | 18,791 | 9,179 | 6.95 | 4.67 | 2.28
2001 | 4,026,036 | 27,523 | 18,275 | 9,248 | 6.84 | 4.54 | 2.30
2000 | 4,058,882 | 27,961 | 18,733 | 9,227 | 6.89 | 4.62 | 2.27
1999 | 3,959,417 | 27,865 | 18,701 | 9,164 | 7.04 | 4.72 | 2.31
1998 | 3,941,553 | 28,325 | 18,915 | 9,410 | 7.19 | 4.80 | 2.39
1997 | 3,880,894 | 27,968 | 18,507 | 9,461 | 7.21 | 4.77 | 2.44
1996 | 3,891,494 | 28,419 | 18,556 | 9,863 | 7.30 | 4.77 | 2.53
1995 | 3,899,589 | 29,505 | 19,186 | 10,319 | 7.57 | 4.92 | 2.65
Non-Hispanic, single race
American Indian and Alaska Native:
2022 | 25,721 | 233 | 135 | 98 | 9.06 | 5.25 | 3.81
2021 | 26,124 | 195 | 100 | 96 | 7.46 | 3.83 | 3.67
2020 | 26,813 | 206 | 102 | 104 | 7.68 | 3.80 | 3.88
2019 | 28,450 | 224 | 114 | 110 | 7.87 | 4.01 | 3.87
2018 | 29,092 | 237 | 120 | 117 | 8.15 | 4.12 | 4.02
2017 | 29,957 | 276 | 143 | 132 | 9.21 | 4.77 | 4.41
Asian:
2022 | 218,994 | 768 | 542 | 225 | 3.51 | 2.47 | 1.03
2021 | 213,813 | 788 | 594 | 193 | 3.69 | 2.78 | 0.90
2020 | 219,068 | 688 | 503 | 185 | 3.14 | 2.30 | 0.84
2019 | 238,769 | 806 | 602 | 204 | 3.38 | 2.52 | 0.85
2018 | 240,798 | 874 | 643 | 231 | 3.63 | 2.67 | 0.96
2017 | 249,250 | 943 | 675 | 268 | 3.78 | 2.71 | 1.08
Black:
2022 | 511,439 | 5,573 | 3,296 | 2,277 | 10.90 | 6.44 | 4.45
2021 | 517,889 | 5,463 | 3,291 | 2,172 | 10.55 | 6.35 | 4.19
2020 | 529,811 | 5,501 | 3,472 | 2,028 | 10.38 | 6.55 | 3.83
2019 | 548,075 | 5,821 | 3,754 | 2,067 | 10.62 | 6.85 | 3.77
2018 | 552,029 | 5,933 | 3,897 | 2,037 | 10.75 | 7.06 | 3.69
2017 | 560,715 | 6,152 | 4,012 | 2,140 | 10.97 | 7.16 | 3.82
Native Hawaiian or Other Pacific Islander:
2022 | 10,122 | 86 | 48 | 38 | 8.50 | 4.74 | 3.75
2021 | 9,531 | 74 | 41 | 32 | 7.76 | 4.30 | 3.36
2020 | 9,626 | 69 | 41 | 27 | 7.17 | 4.26 | 2.80
2019 | 9,770 | 80 | 49 | 31 | 8.19 | 5.02 | 3.17
2018 | 9,476 | 89 | 51 | 38 | 9.39 | 5.38 | 4.01
2017 | 9,426 | 72 | 36 | 36 | 7.64 | 3.82 | 3.82
White:
2022 | 1,840,739 | 8,324 | 5,318 | 3,006 | 4.52 | 2.89 | 1.63
2021 | 1,887,656 | 8,236 | 5,251 | 2,984 | 4.36 | 2.78 | 1.58
2020 | 1,843,432 | 8,115 | 5,290 | 2,825 | 4.40 | 2.87 | 1.53
2019 | 1,915,912 | 8,603 | 5,589 | 3,014 | 4.49 | 2.92 | 1.57
2018 | 1,956,413 | 9,059 | 5,873 | 3,186 | 4.63 | 3.00 | 1.63
2017 | 1,992,461 | 9,306 | 6,061 | 3,246 | 4.67 | 3.04 | 1.63
Hispanic
2022 | 937,421 | 4,581 | 3,138 | 1,442 | 4.89 | 3.35 | 1.54
2021 | 885,916 | 4,246 | 2,899 | 1,347 | 4.79 | 3.27 | 1.52
2020 | 866,713 | 4,063 | 2,828 | 1,235 | 4.69 | 3.26 | 1.42
2019 | 886,467 | 4,462 | 3,091 | 1,371 | 5.03 | 3.49 | 1.55
2018 | 886,210 | 4,303 | 3,036 | 1,267 | 4.86 | 3.43 | 1.43
2017 | 898,764 | 4,583 | 3,198 | 1,383 | 5.10 | 3.56 | 1.54
Central and South American:
2022 | 207,843 | 907 | 652 | 255 | 4.36 | 3.14 | 1.23
2021 | 178,067 | 748 | 521 | 227 | 4.20 | 2.93 | 1.27
2020 | 169,811 | 659 | 470 | 189 | 3.88 | 2.77 | 1.11
2019 | 165,229 | 749 | 535 | 214 | 4.53 | 3.24 | 1.30
2018 | 147,430 | 592 | 438 | 154 | 4.02 | 2.97 | 1.04
2017 | 145,614 | 653 | 465 | 188 | 4.48 | 3.19 | 1.29
Cuban:
2022 | 26,390 | 104 | 65 | 39 | 3.94 | 2.46 | 1.48
2021 | 24,437 | 87 | 68 | 19 | 3.56 | 2.78 | *
2020 | 23,188 | 98 | 63 | 34 | 4.23 | 2.72 | 1.47
2019 | 23,668 | 98 | 65 | 33 | 4.14 | 2.75 | 1.39
2018 | 23,471 | 90 | 64 | 26 | 3.83 | 2.73 | 1.11
2017 | 23,362 | 93 | 69 | 24 | 3.98 | 2.95 | 1.03
Dominican:
2022 | 33,531 | 159 | 112 | 46 | 4.74 | 3.34 | 1.37
2021 | 33,373 | 109 | 68 | 41 | 3.27 | 2.04 | 1.23
2020 | 31,596 | 143 | 101 | 42 | 4.53 | 3.20 | 1.33
2019 | 32,483 | 153 | 111 | 42 | 4.71 | 3.42 | 1.29
Mexican:
2022 | 510,194 | 2,442 | 1,688 | 754 | 4.79 | 3.31 | 1.48
2021 | 485,127 | 2,380 | 1,633 | 747 | 4.91 | 3.37 | 1.54
2020 | 480,531 | 2,264 | 1,586 | 678 | 4.71 | 3.30 | 1.41
2019 | 496,716 | 2,462 | 1,693 | 769 | 4.96 | 3.41 | 1.55
2018 | 495,831 | 2,426 | 1,690 | 736 | 4.89 | 3.41 | 1.48
2017 | 512,126 | 2,588 | 1,795 | 792 | 5.05 | 3.50 | 1.55
Puerto Rican:
2022 | 69,266 | 438 | 267 | 171 | 6.32 | 3.85 | 2.47
2021 | 70,729 | 428 | 278 | 151 | 6.05 | 3.93 | 2.13
2020 | 69,763 | 437 | 308 | 129 | 6.26 | 4.41 | 1.85
2019 | 70,950 | 438 | 294 | 144 | 6.17 | 4.14 | 2.03
2018 | 71,614 | 402 | 290 | 112 | 5.61 | 4.05 | 1.56
2017 | 70,813 | 459 | 307 | 151 | 6.48 | 4.34 | 2.13

* Estimate does not meet National Center for Health Statistics standards of reliability.

NOTES: People of Hispanic origin may be of any race. Infant deaths are weighted to adjust for the 1.1% of infant death records not linked to their corresponding birth certificates. The neonatal and postneonatal mortality rates combined may not exactly add to totals due to rounding. Data for infants of Dominican women are available starting with the 2019 period linked birth/infant death data files.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Race and Hispanic origin

- The mortality rate for infants of American Indian and Alaska Native women increased from 7.46 infant deaths per 1,000 births to 9.06 from 2021 to 2022, and the rate for infants of White women increased from 4.36 to 4.52 (Tables 1 and 2, Figure 2). Increases in rates for infants born to Black (10.55 to 10.90), Hispanic (4.79 to 4.89), and Native Hawaiian or Other Pacific Islander (7.76 to 8.50) women were not significant. The decline in the rate for infants born to Asian women (3.69 to 3.51) was not significant.
- Among Hispanic-origin subgroups, the mortality rate for infants of Dominican women increased from 3.27 to 4.74 from 2021 to 2022; increases in mortality rates for infants of Central and South American (4.20 to 4.36), Cuban (3.56 to 3.94), and Puerto Rican (6.05 to 6.32) women were not significant. The decline in the mortality rate for infants of Mexican women (4.91 to 4.79) from 2021 to 2022 was not significant.
- In 2022, infant mortality continued to vary by race: infants of Black women had the highest mortality rate (10.90), followed by infants of American Indian and Alaska Native and Native Hawaiian or Other Pacific Islander (9.06 and 8.50, respectively), Hispanic (4.89), White (4.52), and Asian (3.51) women.
- Infants of Black women also had the highest neonatal mortality rate in 2022 (6.44) compared with infants of the other race and Hispanic-origin groups; the lowest mortality rate was for infants of Asian women (2.47) (Table 2).
- In 2022, postneonatal mortality rates were higher for infants of Black (4.45), American Indian and Alaska Native (3.81), and Native Hawaiian or Other Pacific Islander (3.75) women than for infants of White (1.63), Hispanic (1.54), and Asian (1.03) women.
- Among Hispanic-origin subgroups in 2022, the mortality rate for infants of Puerto Rican women (6.32) was higher than that of infants of Mexican (4.79), Dominican (4.74), Central and South American (4.36), and Cuban (3.94) women.

Figure 2 Infant mortality rate, by maternal race and Hispanic origin: United States, 2021 and 2022

^1^Significantly different from 2021 (p < 0.05).

^2^People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 2 is a bar graph showing infant mortality rates by maternal race and Hispanic origin for 2021 and 2022.

Table 2

Infant mortality rate, live births, and infant deaths, by selected characteristics and maternal race and Hispanic origin: United States, 2022

Characteristic | Total | Non-Hispanic | | | | | Hispanic
Characteristic | Total | American Indian and Alaska Native^1^ | Asian | Black | Native Hawaiian or Other Pacific Islander | White | Total^2^ | Central and South American | Cuban | Dominican | Mexican | Puerto Rican
| Infant deaths per 1,000 live births in specified group
Total | 5.61 | 9.06 | 3.51 | 10.90 | 8.50 | 4.52 | 4.89 | 4.36 | 3.94 | 4.74 | 4.79 | 6.32
Age at death (days)
Total neonatal | 3.59 | 5.25 | 2.47 | 6.44 | 4.74 | 2.89 | 3.35 | 3.14 | 2.46 | 3.34 | 3.31 | 3.85
Early neonatal (less than 7) | 2.81 | 3.73 | 2.01 | 5.05 | 3.36 | 2.23 | 2.65 | 2.47 | 1.74 | 2.77 | 2.61 | 3.06
Late neonatal (7–27) | 0.78 | 1.48 | 0.47 | 1.40 | * | 0.66 | 0.70 | 0.67 | * | * | 0.70 | 0.79
Postneonatal (28–364) | 2.02 | 3.81 | 1.03 | 4.45 | 3.75 | 1.63 | 1.54 | 1.23 | 1.48 | 1.37 | 1.48 | 2.47
Sex
Male | 6.08 | 10.56 | 3.87 | 11.80 | 8.39 | 4.89 | 5.30 | 4.67 | 4.16 | 4.83 | 5.18 | 6.93
Female | 5.12 | 7.51 | 3.12 | 9.96 | 8.40 | 4.13 | 4.46 | 4.06 | 3.64 | 4.65 | 4.38 | 5.69
Period of gestation (weeks)
Less than 37 | 34.78 | 37.71 | 25.79 | 50.86 | 41.39 | 28.77 | 32.86 | 31.16 | 25.70 | 35.17 | 32.49 | 37.29
Less than 34 | 107.94 | 110.45 | 91.06 | 130.27 | 129.45 | 94.39 | 105.21 | 103.36 | 79.94 | 105.75 | 104.82 | 111.61
Less than 28 | 364.37 | 373.68 | 362.49 | 352.45 | 482.76 | 365.71 | 357.16 | 359.10 | 295.86 | 330.77 | 356.90 | 361.16
28–31 | 43.88 | * | 28.64 | 46.09 | * | 44.52 | 42.83 | 47.47 | * | * | 44.37 | 35.51
32–33 | 21.05 | * | 12.64 | 25.77 | * | 20.83 | 18.54 | 20.50 | * | * | 17.91 | *
34–36 | 8.29 | 12.12 | 4.67 | 10.83 | * | 7.91 | 7.60 | 7.49 | * | * | 7.73 | 8.07
37–41 | 2.18 | 4.74 | 1.21 | 3.97 | 3.84 | 1.95 | 1.72 | 1.51 | 1.64 | 1.29 | 1.68 | 2.29
37–38 | 3.22 | 7.63 | 1.65 | 5.32 | * | 3.03 | 2.42 | 2.25 | * | * | 2.39 | 3.02
39–40 | 1.66 | 3.11 | 0.98 | 3.13 | * | 1.47 | 1.36 | 1.15 | 1.50 | 1.21 | 1.32 | 1.83
41 | 1.73 | * | * | 3.11 | * | 1.53 | 1.52 | * | * | * | 1.37 | *
42 or more | 4.23 | * | – | * | – | 3.52 | * | * | – | – | * | –
Birthweight (grams)
Less than 2,500 | 42.36 | 54.63 | 26.19 | 51.42 | 55.56 | 38.26 | 42.18 | 41.27 | 32.53 | 38.41 | 42.96 | 41.71
Less than 1,500 | 195.53 | 221.08 | 166.60 | 201.31 | 258.28 | 185.46 | 197.41 | 200.26 | 151.35 | 177.98 | 198.39 | 197.46
1,500–2,499 | 13.09 | 20.20 | 6.42 | 14.19 | * | 13.60 | 12.67 | 13.23 | * | * | 13.72 | 9.47
2,500 or more | 2.10 | 4.65 | 1.11 | 3.78 | 4.00 | 1.90 | 1.67 | 1.43 | 1.56 | 1.38 | 1.60 | 2.40
2,500–4,499 | 2.09 | 4.69 | 1.10 | 3.76 | 3.95 | 1.90 | 1.65 | 1.43 | 1.49 | 1.39 | 1.58 | 2.38
4,500 or more | 2.64 | * | * | * | * | 1.84 | 3.16 | * | * | – | * | *
Plurality
Single births | 5.10 | 8.79 | 3.24 | 9.79 | 8.39 | 4.11 | 4.49 | 4.03 | 3.82 | 3.91 | 4.40 | 5.84
Twin births | 20.20 | * | 13.33 | 34.07 | * | 15.59 | 19.57 | 18.49 | * | 32.36 | 19.27 | 20.42
Triplet and higher-order births | 59.76 | * | * | 104.32 | – | 47.77 | 45.22 | * | – | – | * | *
Age of mother
Younger than 15 | 14.25 | * | * | * | – | * | * | * | – | – | – | –
15–19 | 9.86 | * | * | 13.94 | * | 10.53 | 6.93 | 5.45 | * | * | 5.95 | 9.77
20–24 | 7.13 | 9.50 | 4.39 | 12.15 | * | 6.48 | 5.03 | 3.85 | * | 5.61 | 4.79 | 7.24
25–29 | 5.37 | 7.70 | 4.02 | 10.75 | 11.32 | 4.31 | 4.35 | 4.26 | 3.36 | 3.85 | 4.06 | 6.25
30–34 | 4.59 | 8.22 | 3.31 | 9.46 | 9.03 | 3.70 | 4.29 | 4.02 | 2.97 | 3.83 | 4.33 | 5.83
35–39 | 4.99 | 11.83 | 3.10 | 10.53 | * | 3.65 | 5.44 | 4.67 | 5.41 | 4.36 | 5.97 | 4.32
40–54 | 6.73 | * | 3.94 | 11.23 | * | 5.38 | 6.84 | 6.47 | * | * | 7.71 | *
Mother’s place of birth
50 states or District of Columbia | 5.87 | 9.06 | 3.73 | 11.56 | 8.90 | 4.58 | 5.23 | 4.45 | 5.02 | 5.87 | 4.83 | 6.71
Elsewhere | 4.49 | * | 3.40 | 7.65 | 8.10 | 3.40 | 4.41 | 4.33 | 3.11 | 4.15 | 4.66 | 5.00
| Live births
Total | 3,667,758 | 25,721 | 218,994 | 511,439 | 10,122 | 1,840,739 | 937,421 | 207,843 | 26,390 | 33,531 | 510,194 | 69,266
Sex
Male | 1,874,446 | 13,063 | 112,726 | 259,987 | 5,243 | 942,920 | 477,401 | 106,018 | 13,475 | 16,987 | 259,794 | 35,352
Female | 1,793,312 | 12,658 | 106,268 | 251,452 | 4,879 | 897,819 | 460,020 | 101,825 | 12,915 | 16,544 | 250,400 | 33,914
Period of gestation (weeks)
Less than 37 | 380,548 | 3,235 | 20,127 | 74,553 | 1,208 | 173,638 | 94,306 | 19,670 | 2,490 | 3,355 | 51,086 | 7,937
Less than 34 | 101,167 | 842 | 4,920 | 24,986 | 309 | 41,902 | 24,408 | 4,857 | 713 | 974 | 13,032 | 2,240
Less than 28 | 23,369 | 190 | 1,029 | 7,496 | 58 | 7,968 | 5,653 | 1,061 | 169 | 260 | 2,984 | 587
28–31 | 33,663 | 284 | 1,676 | 7,984 | 110 | 14,062 | 8,289 | 1,601 | 224 | 303 | 4,575 | 704
32–33 | 44,135 | 368 | 2,215 | 9,506 | 141 | 19,872 | 10,466 | 2,195 | 320 | 411 | 5,473 | 949
34–36 | 279,381 | 2,393 | 15,207 | 49,567 | 899 | 131,736 | 69,898 | 14,813 | 1,777 | 2,381 | 38,054 | 5,697
37–41 | 3,275,078 | 22,346 | 198,619 | 435,385 | 8,852 | 1,660,116 | 841,129 | 187,675 | 23,851 | 30,145 | 458,026 | 61,202
37–38 | 1,074,082 | 8,124 | 69,213 | 167,263 | 3,075 | 509,163 | 282,083 | 61,782 | 7,451 | 9,734 | 154,002 | 21,164
39–40 | 2,027,670 | 13,198 | 122,060 | 249,451 | 5,239 | 1,053,269 | 517,597 | 116,068 | 15,365 | 18,982 | 281,389 | 37,245
41 | 173,326 | 1,024 | 7,346 | 18,671 | 538 | 97,684 | 41,449 | 9,825 | 1,035 | 1,429 | 22,635 | 2,793
42 or more | 9,461 | 80 | 194 | 1,175 | 39 | 5,974 | 1,565 | 392 | 43 | 24 | 856 | 98
Not stated | 2,671 | 60 | 54 | 326 | 23 | 1,011 | 421 | 106 | 6 | 7 | 226 | 29
Birthweight (grams)
Less than 2,500 | 316,381 | 2,270 | 20,619 | 75,686 | 864 | 131,368 | 73,996 | 15,120 | 1,998 | 2,994 | 39,129 | 6,881
Less than 1,500 | 50,760 | 389 | 2,545 | 15,061 | 151 | 18,850 | 11,818 | 2,272 | 370 | 545 | 6,195 | 1,180
1,500–2,499 | 265,621 | 1,881 | 18,074 | 60,625 | 713 | 112,518 | 62,178 | 12,848 | 1,628 | 2,449 | 32,934 | 5,701
2,500 or more | 3,350,350 | 23,447 | 198,357 | 435,642 | 9,257 | 1,709,108 | 863,368 | 192,707 | 24,388 | 30,534 | 471,042 | 62,378
2,500–4,499 | 3,317,042 | 23,047 | 197,470 | 432,932 | 9,116 | 1,689,020 | 855,451 | 191,128 | 24,137 | 30,297 | 466,357 | 61,872
4,500 or more | 33,308 | 400 | 887 | 2,710 | 141 | 20,088 | 7,917 | 1,579 | 251 | 237 | 4,685 | 506
Not stated | 1,027 | 4 | 18 | 111 | 1 | 263 | 57 | 16 | 4 | 3 | 23 | 7
Plurality
Single births | 3,550,380 | 25,024 | 213,707 | 489,720 | 9,890 | 1,779,221 | 913,854 | 203,473 | 25,666 | 32,521 | 497,316 | 67,099
Twin births | 114,483 | 682 | 5,177 | 21,163 | 232 | 59,969 | 22,992 | 4,272 | 711 | 989 | 12,560 | 2,106
Triplet and higher-order births | 2,895 | 15 | 110 | 556 | – | 1,549 | 575 | 98 | 13 | 21 | 318 | 61
Age of mother
Younger than 15 | 1,825 | 32 | 4 | 482 | 4 | 407 | 796 | 284 | 2 | 14 | 360 | 42
15–19 | 143,789 | 1,924 | 982 | 29,194 | 431 | 48,060 | 56,566 | 12,659 | 582 | 1,235 | 32,116 | 4,093
20–24 | 638,685 | 6,736 | 10,016 | 110,822 | 2,609 | 276,137 | 206,948 | 41,251 | 3,863 | 6,243 | 118,647 | 16,429
25–29 | 1,013,417 | 7,275 | 42,087 | 142,234 | 2,915 | 515,204 | 270,357 | 55,454 | 7,136 | 9,607 | 151,390 | 20,792
30–34 | 1,118,787 | 6,202 | 89,679 | 133,896 | 2,435 | 615,589 | 237,703 | 54,524 | 9,086 | 9,666 | 124,391 | 17,488
35–39 | 606,598 | 2,873 | 61,259 | 73,610 | 1,375 | 318,572 | 129,675 | 33,630 | 4,805 | 5,275 | 65,649 | 8,330
40–54 | 144,657 | 679 | 14,967 | 21,201 | 353 | 66,770 | 35,376 | 10,041 | 916 | 1,491 | 17,641 | 2,092
Mother’s place of birth
50 states or District of Columbia | 2,826,844 | 25,287 | 52,052 | 416,374 | 3,706 | 1,714,360 | 510,450 | 40,690 | 10,951 | 10,569 | 329,693 | 49,898
Elsewhere | 832,728 | 383 | 166,347 | 93,181 | 6,295 | 123,568 | 425,599 | 166,937 | 15,414 | 22,880 | 180,061 | 19,018
Not stated | 8,186 | 51 | 595 | 1,884 | 121 | 2,811 | 1,372 | 216 | 25 | 82 | 440 | 350
| Infant deaths
Total | 20,577 | 233 | 768 | 5,573 | 86 | 8,324 | 4,581 | 907 | 104 | 159 | 2,442 | 438
Age at death (days)
Total neonatal | 13,158 | 135 | 542 | 3,296 | 48 | 5,318 | 3,138 | 652 | 65 | 112 | 1,688 | 267
Early neonatal (less than 7) | 10,304 | 96 | 441 | 2,582 | 34 | 4,104 | 2,482 | 513 | 46 | 93 | 1,332 | 212
Late neonatal (7–27) | 2,854 | 38 | 102 | 714 | 14 | 1,214 | 657 | 139 | 19 | 19 | 356 | 55
Postneonatal (28–364) | 7,419 | 98 | 225 | 2,277 | 38 | 3,006 | 1,442 | 255 | 39 | 46 | 754 | 171
Sex
Male | 11,391 | 138 | 436 | 3,069 | 44 | 4,613 | 2,529 | 495 | 56 | 82 | 1,345 | 245
Female | 9,186 | 95 | 332 | 2,504 | 41 | 3,712 | 2,052 | 413 | 47 | 77 | 1,096 | 193
Period of gestation (weeks)
Less than 37 | 13,235 | 122 | 519 | 3,792 | 50 | 4,996 | 3,099 | 613 | 64 | 118 | 1,660 | 296
Less than 34 | 10,920 | 93 | 448 | 3,255 | 40 | 3,955 | 2,568 | 502 | 57 | 103 | 1,366 | 250
Less than 28 | 8,515 | 71 | 373 | 2,642 | 28 | 2,914 | 2,019 | 381 | 50 | 86 | 1,065 | 212
28–31 | 1,477 | 11 | 48 | 368 | 10 | 626 | 355 | 76 | 5 | 10 | 203 | 25
32–33 | 929 | 11 | 28 | 245 | 2 | 414 | 194 | 45 | 2 | 7 | 98 | 12
34–36 | 2,315 | 29 | 71 | 537 | 9 | 1,042 | 531 | 111 | 7 | 15 | 294 | 46
37–41 | 7,124 | 106 | 241 | 1,729 | 34 | 3,241 | 1,449 | 284 | 39 | 39 | 770 | 140
37–38 | 3,460 | 62 | 114 | 890 | 18 | 1,543 | 684 | 139 | 13 | 13 | 368 | 64
39–40 | 3,364 | 41 | 120 | 782 | 14 | 1,550 | 702 | 133 | 23 | 23 | 372 | 68
41 | 300 | 2 | 6 | 58 | 2 | 149 | 63 | 12 | 3 | 3 | 31 | 7
42 or more | 40 | 1 | – | 9 | – | 21 | 6 | 1 | – | – | 2 | –
Not stated | 179 | 4 | 8 | 43 | 2 | 66 | 27 | 9 | 1 | 1 | 9 | 2
Birthweight (grams)
Less than 2,500 | 13,402 | 124 | 540 | 3,892 | 48 | 5,026 | 3,121 | 624 | 65 | 115 | 1,681 | 287
Less than 1,500 | 9,925 | 86 | 424 | 3,032 | 39 | 3,496 | 2,333 | 455 | 56 | 97 | 1,229 | 233
1,500–2,499 | 3,478 | 38 | 116 | 860 | 8 | 1,530 | 788 | 170 | 9 | 18 | 452 | 54
2,500 or more | 7,037 | 109 | 221 | 1,646 | 37 | 3,252 | 1,439 | 275 | 38 | 42 | 753 | 150
2,500–4,499 | 6,949 | 108 | 217 | 1,629 | 36 | 3,215 | 1,414 | 273 | 36 | 42 | 738 | 147
4,500 or more | 88 | 1 | 4 | 17 | 1 | 37 | 25 | 2 | 2 | – | 15 | 3
Not stated | 138 | – | 7 | 36 | 1 | 46 | 20 | 8 | 1 | 1 | 8 | 1
Plurality
Single births | 18,091 | 220 | 692 | 4,794 | 83 | 7,315 | 4,106 | 821 | 98 | 127 | 2,187 | 392
Twin births | 2,313 | 9 | 69 | 721 | 3 | 935 | 450 | 79 | 6 | 32 | 242 | 43
Triplet and higher-order births | 173 | 4 | 6 | 58 | – | 74 | 26 | 7 | – | – | 12 | 3
Age of mother
Younger than 15 | 26 | 1 | 1 | 9 | – | 9 | 4 | 2 | – | – | – | –
15–19 | 1,418 | 19 | 8 | 407 | 3 | 506 | 392 | 69 | 6 | 18 | 191 | 40
20–24 | 4,553 | 64 | 44 | 1,347 | 11 | 1,790 | 1,041 | 159 | 17 | 35 | 568 | 119
25–29 | 5,446 | 56 | 169 | 1,529 | 33 | 2,223 | 1,177 | 236 | 24 | 37 | 615 | 130
30–34 | 5,137 | 51 | 297 | 1,267 | 22 | 2,275 | 1,019 | 219 | 27 | 37 | 539 | 102
35–39 | 3,024 | 34 | 190 | 775 | 11 | 1,162 | 706 | 157 | 26 | 23 | 392 | 36
40–54 | 973 | 6 | 59 | 238 | 5 | 359 | 242 | 65 | 3 | 9 | 136 | 10
Mother’s place of birth
50 states or District of Columbia | 16,593 | 229 | 194 | 4,814 | 33 | 7,848 | 2,669 | 181 | 55 | 62 | 1,592 | 335
Elsewhere | 3,741 | 2 | 565 | 713 | 51 | 420 | 1,877 | 723 | 48 | 95 | 839 | 95
Not stated | 244 | 2 | 9 | 47 | 1 | 56 | 35 | 4 | – | 2 | 11 | 8

* Figure does not meet National Center for Health Statistics standards of reliability; based on fewer than 20 deaths in the numerator.

– Quantity zero.

1 Includes Aleut and Eskimo people.

2 Includes other and unknown Hispanic origin not stated and not shown separately.

NOTES: Infant deaths are weighted so numbers may not exactly add to totals due to rounding. Not stated responses were included in totals but were not distributed among groups for rate computations. Race and Hispanic origin are reported separately on birth certificates. Race categories are consistent with the 1997 Office of Management and Budget standards. People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Maternal age

- The mortality rate for infants of women ages 25–29 increased from 2021 to 2022 (5.15 infant deaths per 1,000 births to 5.37) (Figure 3, Table 2). Increases in rates for infants of females ages 15–19 (9.15 to 9.86), 20–24 (6.87 to 7.13), 30–34 (4.48 to 4.59), and 35–39 (4.92 to 4.99) were not significant.
- Nonsignificant declines were seen for infants of females younger than 15 (14.92 to 14.25) and for infants of women age 40 and older (6.74 to 6.73).
- In 2022, mortality rates were highest for infants of females younger than age 15 and ages 15–19 (14.25 and 9.86, respectively), decreased to a low of 4.59 for infants of women ages 30–34, and then increased to 6.73 for infants of women age 40 and older.

Figure 3 Infant mortality rate, by maternal age: United States, 2021 and 2022

^1^Significantly different from 2021 (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 3 is a bar graph showing infant mortality rates by maternal age for 2021 and 2022.

### Gestational age

- Mortality rates increased among preterm infants overall (less than 37 weeks of gestation) from 2021 to 2022, from 33.59 deaths per 1,000 live births to 34.78 (Table, Table 2). Increases were seen among early preterm infants (less than 34 weeks of gestation), from 103.08 to 107.94; the increase for infants born at 34–36 weeks (8.11 to 8.29) was not significant.
- Mortality rates also rose for infants born at term, or at 37–41 weeks (2.08 to 2.18). The increase in the rate at 42 weeks or more (3.79 to 4.23) was nonsignificant.
- In 2022, 65% of infant deaths occurred among infants born preterm (less than 37 weeks of gestation), unchanged from 2021.

Table

Infant mortality rate, by gestational age: United States, 2015–2022

Year | Less than 32 weeks | 32–33 weeks | 34–36 weeks | 37–41 weeks | 42 weeks or more
| Deaths per 1,000 live births
2022 | 175.18 | 21.05 | 8.29 | 2.18 | 4.23
2021 | 167.39 | 19.35 | 8.11 | 2.08 | 3.79
2020 | 175.88 | 20.11 | 7.92 | 2.04 | 4.17
2019 | 180.40 | 19.21 | 8.21 | 2.03 | 5.72
2018 | 185.79 | 21.95 | 8.21 | 2.05 | 5.39
2017 | 187.56 | 20.50 | 8.50 | 2.10 | 3.98
2016 | 190.15 | 20.12 | 8.65 | 2.19 | 4.31
2015 | 193.54 | 20.79 | 8.76 | 2.17 | 4.20

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Leading causes of infant death

- In 2022, the five leading causes of all infant deaths were the same as those in 2021: congenital malformations (19.5% of infant deaths), disorders related to short gestation and low birth weight (14.0%), sudden infant death syndrome (SIDS) (7.4%), unintentional injuries (6.6%), and maternal complications (5.9%) (Table 3).
- From 2021 to 2022, the infant mortality rate increased for maternal complications (from 30.4 infant deaths per 100,000 live births to 33.1).
- The increases in rates for congenital malformations (108.9 to 109.2), SIDS (39.8 to 41.7), and unintentional injuries (35.5 to 36.8), and the decline for disorders related to short gestation and low birth weight (80.7 to 78.6) were not significant (Table 3).
- Congenital malformations was the leading cause of death for infants born to American Indian and Alaska Native (178.8), Asian (70.3), White (99.6), and Hispanic (119.5) women in 2022 (Table 4).
- In 2022, disorders related to short gestation and low birth weight was the leading cause of death for infants of Black women (188.1).

Table 3

Infant deaths, percentage of deaths, and infant mortality rate, by five leading causes of infant death: United States, 2010–2022

Year | Congenital malformations (Q00–Q99) | | | Short gestation and low birthweight,not elsewhere classified (P07) | | | Sudden infant death syndrome (R95) | | | Accidents (unintentional injuries) (V01–X59) | | | Maternal complications of pregnancy (P01)
Year | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births) | Number | Percent | Rate (deaths per 100,000 live births)
2022 | 4,004 | 19.5 | 109.2 | 2,884 | 14.0 | 78.6 | 1,531 | 7.4 | 41.7 | 1,351 | 6.6 | 36.8 | 1,213 | 5.9 | 33.1
2021 | 3,990 | 20.0 | 108.9 | 2,957 | 14.8 | 80.7 | 1,458 | 7.3 | 39.8 | 1,300 | 6.5 | 35.5 | 1,113 | 5.6 | 30.4
2020 | 4,047 | 20.7 | 112.0 | 3,152 | 16.1 | 87.2 | 1,386 | 7.1 | 38.4 | 1,192 | 6.1 | 33.0 | 1,115 | 5.7 | 30.9
2019 | 4,313 | 20.6 | 115.1 | 3,460 | 16.5 | 92.3 | 1,251 | 6.0 | 33.4 | 1,264 | 6.0 | 33.7 | 1,250 | 6.0 | 33.4
2018 | 4,501 | 20.9 | 118.7 | 3,683 | 17.1 | 97.1 | 1,331 | 6.2 | 35.1 | 1,169 | 5.4 | 30.8 | 1,371 | 6.4 | 36.2
2017 | 4,596 | 20.6 | 119.2 | 3,757 | 16.8 | 97.4 | 1,360 | 6.1 | 35.3 | 1,313 | 5.9 | 34.1 | 1,436 | 6.4 | 37.2
2016 | 4,823 | 20.8 | 122.2 | 3,926 | 17.0 | 99.5 | 1,498 | 6.5 | 38.0 | 1,217 | 5.3 | 30.8 | 1,407 | 6.1 | 35.7
2015 | 4,847 | 20.7 | 121.8 | 4,087 | 17.4 | 102.7 | 1,567 | 6.7 | 39.4 | 1,289 | 5.5 | 32.4 | 1,527 | 6.5 | 38.4
2014 | 4,754 | 20.5 | 119.2 | 4,172 | 18.0 | 104.6 | 1,541 | 6.6 | 38.6 | 1,163 | 5.0 | 29.2 | 1,580 | 6.8 | 39.6
2013 | 4,778 | 20.4 | 121.5 | 4,213 | 18.0 | 107.1 | 1,561 | 6.7 | 39.7 | 1,150 | 4.9 | 29.2 | 1,597 | 6.8 | 40.6
2012 | 4,967 | 21.0 | 125.7 | 4,214 | 17.8 | 106.6 | 1,676 | 7.1 | 42.4 | 1,163 | 4.9 | 29.4 | 1,518 | 6.4 | 38.4
2011 | 5,016 | 20.9 | 126.9 | 4,115 | 17.1 | 104.1 | 1,905 | 7.9 | 48.2 | 1,167 | 4.9 | 29.5 | 1,598 | 6.7 | 40.4
2010 | 5,115 | 20.8 | 127.9 | 4,151 | 16.9 | 103.8 | 2,058 | 8.4 | 51.5 | 1,107 | 4.5 | 27.7 | 1,563 | 6.4 | 39.1

NOTE: The five leading causes of death (based on International Classification of Diseases, 10th Revision, 1992) were the same for 2010–2020, but ranking changed in 2020 compared with previous years.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Table 4

Infant deaths and mortality rate for the five leading causes of infant death, by maternal race and Hispanic origin: United States, 2022 [Rates are per 100,000 live births in specified group]

Cause of death (based on International Classification of Diseases, 10th Revision, 1992) | All races | | | Non-Hispanic
Cause of death (based on International Classification of Diseases, 10th Revision, 1992) | All races | | | American Indian and Alaska Native | | | Asian^1^ | | | Black | | | White
Cause of death (based on International Classification of Diseases, 10th Revision, 1992) | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate
All causes | … | 20,577 | 561.0 | … | 233 | 905.9 | … | 768 | 350.7 | … | 5,573 | 1,089.7 | … | 8,324 | 452.2
Congenital malformations,deformations, and chromosomal abnormalities (Q00–Q99) | 1 | 4,004 | 109.2 | 1 | 46 | 178.8 | 1 | 154 | 70.3 | 2 | 690 | 134.9 | 1 | 1,834 | 99.6
Disorders related to short gestationand low birth weight, not elsewhere classified (P07) | 2 | 2,884 | 78.6 | 3 | 19 | * | 2 | 124 | 56.6 | 1 | 962 | 188.1 | 2 | 955 | 51.9
Sudden infant death syndrome (R95) | 3 | 1,531 | 41.7 | 2 | 27 | 105.0 | 7 | 28 | 12.8 | 3 | 542 | 106.0 | 4 | 604 | 32.8
Accidents (unintentionalinjuries) (V01–X59) | 4 | 1,351 | 36.8 | 4 | 17 | * | 5 | 31 | 14.2 | 4 | 417 | 81.5 | 3 | 620 | 33.7
Newborn affected by maternalcomplications of pregnancy (P01) | 5 | 1,213 | 33.1 | 5 | 12 | * | 3 | 68 | 31.1 | 5 | 350 | 68.4 | 5 | 400 | 21.7

Cause of death (based on International Classification of Diseases, 10th Revision, 1992) | Total Hispanic | | | Central and South American^2^ | | | Mexican | | | Puerto Rican
Cause of death (based on International Classification of Diseases, 10th Revision, 1992) | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate | Rank | Number | Rate
All causes | … | 4,581 | 488.7 | … | 907 | 436.4 | … | 2,442 | 478.6 | … | 438 | 632.3
Congenital malformations,deformations, and chromosomal abnormalities (Q00–Q99) | 1 | 1,120 | 119.5 | 1 | 277 | 133.3 | 1 | 634 | 124.3 | 2 | 56 | 80.8
Disorders related to short gestationand low birth weight, not elsewhere classified (P07) | 2 | 650 | 69.3 | 2 | 132 | 63.5 | 2 | 349 | 68.4 | 1 | 62 | 89.5
Sudden infant death syndrome (R95) | 4 | 241 | 25.7 | 4 | 35 | 16.8 | 4 | 110 | 21.6 | 3 | 42 | 60.6
Accidents (unintentionalinjuries) (V01–X59) | 5 | 188 | 20.1 | 9 | 16 | * | 5 | 96 | 18.8 | 4 | 32 | 46.2
Newborn affected by maternalcomplications of pregnancy (P01) | 3 | 291 | 31.0 | 3 | 42 | 20.2 | 3 | 161 | 31.6 | 5 | 30 | 43.3

… Category not applicable.

* Figure does not meet National Center for Health Statistics standards of reliability; based on fewer than 20 deaths in the numerator.

1 For infants born to Asian non-Hispanic women, Bacterial sepsis (P36.9) was the fourth leading cause of death, with 37 deaths and a rate of 16.9.

2 For infants born to Central and South American women, Bacterial sepsis (P36.9) was the fifth leading cause of death, with 30 deaths and a rate of 14.6.

NOTES: Reliable cause-specific infant mortality rates cannot be computed for infants of Native Hawaiian or Other Pacific Islander non-Hispanic, Cuban, or Dominican women because of the small number of infant deaths. Race and Hispanic origin are reported separately on birth certificates. Race categories are consistent with the 1997 Office of Management and Budget standards. People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

### Infant mortality by state

- By state, infant mortality ranged from a low of 3.32 infant deaths per 1,000 births in Massachusetts to a high of 9.11 in Mississippi (Figure 4, Table 5).
- Twelve states had infant mortality rates significantly lower than the national infant mortality rate: California, Colorado, Connecticut, Massachusetts, Minnesota, Nevada, New Hampshire, New Jersey, New York, Oregon, Rhode Island, and Washington.
- Nineteen states had infant mortality rates significantly higher than the U.S. infant mortality rate: Alabama, Arizona, Arkansas, Delaware, Florida, Georgia, Indiana, Louisiana, Michigan, Mississippi, Missouri, North Carolina, Ohio, Oklahoma, South Carolina, South Dakota, Tennessee, Virginia, and West Virginia.

Figure 4 Infant mortality rate, by state: United States, 2022

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

Figure 4 is a US state map showing infant mortality rates by state for 2022.

Table 5

Infant mortality rate: United States and each state, 2022

[By place of residence]

Area | Rate (deaths per1,000 births) | Infant deaths | Live births
United States^1^ | 5.61 | 20,577 | 3,667,758
Alabama | 6.69 | 389 | 58,149
Alaska | 6.62 | 62 | 9,359
Arizona | 6.17 | 485 | 78,547
Arkansas | 7.67 | 272 | 35,471
California | 4.11 | 1,724 | 419,104
Colorado | 4.54 | 283 | 62,383
Connecticut | 4.25 | 150 | 35,332
Delaware | 7.49 | 81 | 10,816
District of Columbia | 5.45 | 44 | 8,075
Florida | 5.98 | 1,342 | 224,433
Georgia | 7.08 | 893 | 126,130
Hawaii | 5.79 | 90 | 15,535
Idaho | 5.27 | 118 | 22,391
Illinois | 5.59 | 718 | 128,350
Indiana | 7.16 | 570 | 79,649
Iowa | 5.20 | 190 | 36,506
Kansas | 5.81 | 200 | 34,401
Kentucky | 5.77 | 302 | 52,315
Louisiana | 7.37 | 416 | 56,479
Maine | 6.37 | 77 | 12,093
Maryland | 6.03 | 415 | 68,782
Massachusetts | 3.32 | 228 | 68,584
Michigan | 6.42 | 657 | 102,321
Minnesota | 4.50 | 288 | 64,015
Mississippi | 9.11 | 316 | 34,675
Missouri | 6.77 | 467 | 68,985
Montana | 4.65 | 52 | 11,175
Nebraska | 5.83 | 142 | 24,345
Nevada | 4.49 | 149 | 33,193
New Hampshire | 3.48 | 42 | 12,077
New Jersey | 3.57 | 367 | 102,893
New Mexico | 5.88 | 127 | 21,614
New York | 4.26 | 885 | 207,774
North Carolina | 6.79 | 825 | 121,562
North Dakota | 4.39 | 42 | 9,567
Ohio | 7.11 | 912 | 128,231
Oklahoma | 6.89 | 333 | 48,332
Oregon | 4.48 | 177 | 39,493
Pennsylvania | 5.69 | 741 | 130,252
Rhode Island | 3.90 | 40 | 10,269
South Carolina | 6.76 | 391 | 57,820
South Dakota | 7.77 | 87 | 11,201
Tennessee | 6.61 | 544 | 82,265
Texas | 5.72 | 2,228 | 389,741
Utah | 5.03 | 230 | 45,768
Vermont | 4.89 | 26 | 5,316
Virginia | 6.21 | 594 | 95,630
Washington | 4.34 | 362 | 83,333
West Virginia | 7.32 | 124 | 16,929
Wisconsin | 5.80 | 348 | 60,049
Wyoming | 5.62 | 34 | 6,049
Puerto Rico | 7.38 | 141 | 19,112
Guam | 10.73 | 27 | 2,517

1 Does not include Puerto Rico or Guam.

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

## Acknowledgments

This report was prepared by the Division of Vital Statistics (DVS) under the general direction of DVS Acting Director Paul Sutton; Robert Anderson, Chief, Statistical Analysis and Surveillance Branch; and Joyce Martin, Team Leader, Perinatal Research and Statistics Team, Statistical Analysis and Surveillance Branch. Rajesh Virkar, Chief of the Information Technology Branch (ITB), and Steve J. Steimel, Annie S. Liu, and Prameela Sathunuru of ITB provided computer programming support. Steve J. Steimel and Annie S. Liu prepared the natality file; Steve J. Steimel, Annie S. Liu, and Prameela Sathunuru prepared the linked birth/infant death data file. The Data Acquisition, Classification, and Evaluation Branch staff of DVS evaluated the quality of and acceptance procedures for the state data files on which this report is based. The National Center for Health Statistics Office of Information Services, Information Design and Publishing Staff, edited and produced this report: editor Jen Hurlburt and typesetter and graphic designer Ebony Davis.

## References

1 National Center for Health Statistics. User guide to the 2022 period/2021 cohort linked birth/infant death public use file. 2023. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/period-cohort-linked/22PE21CO_linkedUG.pdf.
2 Osterman MJK Hamilton BE Martin JA Driscoll AK Valenzuela CP. Births: Final data for 2022. National Vital Statistics Reports; vol 73 no 2. Hyattsville, MD: National Center for Health Statistics. 2024. DOI: 10.15620/cdc:145588.
3 National Center for Health Statistics. User guide to the 2022 natality public use file. 2023. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2022.pdf.
4 Ely DM Driscoll AK. Infant mortality in the United States, 2017: Data from the period linked birth/infant death file. National Vital Statistics Reports; vol 68 no 10. Hyattsville, MD: National Center for Health Statistics. 2019.
5 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist 62(210):58782–90. 1997.
6 National Center for Health Statistics. 2003 revisions of the U.S. Standard Certificates and Reports. 2003. Available from: https://www.cdc.gov/nchs/nvss/vital_certificate_revisions.htm.
7 World Health Organization. International statistical classification of diseases and related health problems, 10th revision (ICD–10). 2nd ed. Geneva, Switzerland. 2004.
8 Kochanek KD Murphy SL Xu JQ Arias E. Deaths: Final data for 2017. National Vital Statistics Reports; vol 68 no 9. Hyattsville, MD: National Center for Health Statistics. 2019. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr68/nvsr68_09-508.pdf.
9 National Center for Health Statistics. U.S. Standard Certificate of Live Birth. 2003. Available from: https://www.cdc.gov/nchs/data/dvs/birth11-03final-ACC.pdf.
10 Xu JQ Murphy SL Kochanek KD Arias E. Deaths: Final data for 2022. National Vital Statistics Reports. Hyattsville, MD: National Center for Health Statistics. 2024. [Forthcoming].
11 Martin JA Osterman MJK Kirmeyer SE Gregory ECW. Measuring gestational age in vital statistics data: Transitioning to the obstetric estimate. National Vital Statistics Reports; vol 64 no 5. Hyattsville, MD: National Center for Health Statistics. 2015.
12 National Center for Health Statistics. Instructions for classifying the underlying cause of death, 2022. NCHS Instruction Manual, part 2a. 2022.
13 National Center for Health Statistics. Vital statistics ICD–10 ACME decision tables for classifying underlying causes of death, 2016. NCHS Instruction Manual, part 2c. 2016.
14 National Center for Health Statistics. Mortality multiple cause-of-death public use data file documentation (published annually). 2022
15 World Health Organization. Manual of the International Statistical Classification of Diseases, Injuries and Causes of Death: Based on the recommendations of the Ninth Revision Conference, 1975, and adopted by the Twenty-ninth World Health Assembly, 1975 revision. Geneva, Switzerland. 1977.
16 National Center for Health Statistics. ICD–10 cause-of-death lists for tabulating mortality statistics (updated September 2020 to include WHO updates to ICD–10 for data year 2020). NCHS Instruction Manual, part 9. 2020.

## Technical Notes

### Data source and 2003 revision

Information on the data source for the linked birth/infant death file is available elsewhere (1). Additionally, further information on the 2003 revision of the birth certificate is available (3); see also the U.S. Standard Certificate of Live Birth (9).

### Weighting

In 2022, a record weight was added to the U.S. linked file to compensate for the 1.4% of infant death records that could not be linked to their corresponding birth certificates. The percentage of records linked varied by registration area, ranging from 94.5% through 100.0% (Table). The number of infant deaths in the linked file for the 50 states and the District of Columbia was weighted to equal the sum of the linked plus unlinked infant deaths by state of occurrence of birth and age at death (younger than 7 days, 7–27 days, and 28 days to younger than 1 year). The addition of the weight reduced the potential for bias in comparing infant mortality rates by maternal and infant characteristics.

Table

Percentage of infant deaths linked to their corresponding birth records, by state of occurrence of death: United States and each state, 2022

Area | Percent linked by state of occurrence of death
United States | 98.6
Alabama | 99.7
Alaska | 100.0
Arizona | 98.3
Arkansas | 100.0
California | 98.0
Colorado | 99.7
Connecticut | 100.0
Delaware | 100.0
District of Columbia | 100.0
Florida | 99.9
Georgia | 100.0
Hawaii | 100.0
Idaho | 100.0
Illinois | 99.9
Indiana | 99.7
Iowa | 100.0
Kansas | 100.0
Kentucky | 97.7
Louisiana | 98.1
Maine | 98.7
Maryland | 100.0
Massachusetts | 99.6
Michigan | 99.1
Minnesota | 100.0
Mississippi | 100.0
Missouri | 98.5
Montana | 100.0
Nebraska | 97.8
Nevada | 99.3
New Hampshire | 100.0
New Jersey | 97.1
New Mexico | 97.2
New York | 99.1
New York City | 100.0
North Carolina | 98.1
North Dakota | 100.0
Ohio | 99.9
Oklahoma | 99.4
Oregon | 100.0
Pennsylvania | 95.8
Rhode Island | 100.0
South Carolina | 100.0
South Dakota | 100.0
Tennessee | 100.0
Texas | 94.5
Utah | 100.0
Vermont | 100.0
Virginia | 99.6
Washington | 100.0
West Virginia | 99.1
Wisconsin | 100.0
Wyoming | 100.0

SOURCE: National Center for Health Statistics, National Vital Statistics System, linked birth/infant death file.

The 2022 linked file initially included 20,613 infant death records. Of these records, 20,334 were linked; 279 were unlinked because corresponding birth certificates could not be identified. The 20,613 linked and unlinked records contained 31 records of infants whose mothers’ usual place of residence was outside of the United States; these records were excluded from linked file analyses for a weighted total of 20,577 infant deaths by place of residence for 2022.

### Comparison of infant mortality data between linked file and vital statistics mortality file

The overall infant mortality rate of 5.61 from the 2022 period linked file is statistically the same as that from the 2022 vital statistics mortality file (5.60) (10). The number of infant deaths in the linked file (20,334) differs slightly from the number in the mortality file (20,553) (10). Differences in numbers of infant deaths between the two data sources are primarily due to geographic coverage differences. For the vital statistics mortality file, all deaths occurring in the 50 states and the District of Columbia are included regardless of the place of birth of the infant. In contrast, to be included in the U.S. linked file, both the birth and death must occur in the 50 states or the District of Columbia (the territory linked file is a separate file). Weighting of the linked file also may contribute to small differences in numbers and rates by specific variables between these two data sets.

### Period of gestation

Beginning with the 2014 data year, the National Center for Health Statistics (NCHS) transitioned to a new standard for estimating the gestational age of the newborn. The new measure—the obstetric estimate of gestation at delivery—replaces the measure based on the date of the last normal menses (11). Accordingly, gestational age data shown in this report are based on the obstetric estimate of gestation at delivery. National data based on obstetric estimate of gestation at delivery data are available only from data year 2007 forward. Information on and discussion of the reasons for the change, as well as a detailed comparison of the two measures, are presented elsewhere (11).

### Sex, birthweight, plurality, and nativity

Detailed definitions and more information on sex, birthweight, plurality, and nativity are available elsewhere (1,3).

### Cause-of-death classification

The mortality statistics presented in this report were compiled in accordance with World Health Organization regulations, which specify that member nations classify and code causes of death according to the current revision of the International Statistical Classification of Diseases (ICD). ICD provides the basic guidance to code and classify causes of death, details disease classification, and supplies definitions, tabulation lists, the format of the death certificate, and the rules for coding cause of death. Cause-of-death data presented in this report were coded by procedures outlined in annual issues of the NCHS Instruction Manual (12,13).

In this report, tabulations of cause-of-death statistics are based solely on the underlying cause of death. Generally, more medical information is reported on death certificates than is directly reflected in the underlying cause of death. This is captured in NCHS multiple cause-of-death statistics (14,15).

### Tabulation lists and cause-of-death ranking

The cause-of-death rankings for ICD–10 are based on the “List of 130 Selected Causes of Infant Death.” The tabulation lists and rules for ranking leading causes of death are published in the NCHS Instruction Manual, Part 9: "ICD–10 Cause-of-death Lists for Tabulating Mortality Statistics" (16).

### Computation of rates

Information on and discussion of computation of rates (1) is also available from the “User Guide to the 2010 Natality Public Use File” at: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2010.pdf.

### Random variation in infant mortality rates

For information and discussion on random variation and significance testing for linked data (1), see also the “User Guide to the 2010 Natality Public Use File” at: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/DVS/natality/UserGuide2010.pdf.

### Availability of linked file

Linked file data are available for download from the Vital Statistics Online Data Portal: https://www.cdc.gov/nchs/data_access/vitalstatsonline.htm. Linked period file data may also be accessed via the Centers for Disease Control and Prevention’s WONDER database, available from: https://wonder.cdc.gov/lbd.html. Beginning with 2005, the public-use file no longer includes geographic detail; such files are available upon special request (see the NCHS Division of Vital Statistics data release policy at: https://www.cdc.gov/nchs/nvss/nvss-restricted-data.htm). Data are also available in issues of Vital and Health Statistics, Series 20; National Vital Statistics Reports; and NCHS Data Briefs from the NCHS website: https://www.cdc.gov/nchs/products/index.htm.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Acting Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/email-updates.htm.

For questions or general information about NCHS: Tel: 1–800–CDC–INFO (1–800–232–4636) • TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs • Online request form: https://www.cdc.gov/info • CS350179