# Volume 73 Number 7 U.S. State Life Tables, 2021

### Objectives

This report presents complete period life tables for each of the 50 states and the District of Columbia by sex based on age-specific death rates in 2021.

### Methods

Data used to prepare the 2021 state-specific life tables include: 2021 final mortality statistics; July 1, 2021, population estimates based on the Blended Base population estimates produced by the U.S. Census Bureau; and 2021 Medicare data for people ages 66–99. The methodology used to estimate the state-specific life tables is the same as that used to estimate the 2021 national life tables, with some modifications.

### Results

Among the 50 states and District of Columbia, Hawaii had the highest life expectancy at birth, 79.9 years in 2021, and Mississippi had the lowest, 70.9 years. From 2020 to 2021, life expectancy at birth declined for 39 states, increased for 11 states, and remained unchanged for the District of Columbia. In 2021, life expectancy at age 65 ranged from 16.1 years in Mississippi to 20.6 years in Hawaii. Life expectancy at birth was higher for females in all states and the District of Columbia. The difference in life expectancy between females and males ranged from 3.9 years in Utah to 7.6 years in New Mexico.

## Introduction

This report presents annual complete period life tables for each of the 50 states and District of Columbia (D.C.) for 2021. Life tables were produced for the total, male, and female populations of each state and D.C. based on age-specific death rates for 2021. The methodology used to estimate the state-specific life tables is the same as that used to estimate the annual U.S. life tables (1), with some minor modifications described in the Technical Notes.

Life tables are of two types: the cohort (or generation) life table and the period (or current) life table. The cohort life table presents the mortality experience of a particular birth cohort—all people born in 1900, for example—from the moment of birth through consecutive ages in successive calendar years. Based on age-specific death rates observed through consecutive calendar years, the cohort life table reflects the mortality experience of an actual cohort from birth until no lives remain in the group. To prepare just a single complete cohort life table requires data over many years. Due to data unavailability or incompleteness (2), constructing cohort life tables based entirely on observed data for real cohorts is usually not feasible. For instance, a life table representation of the mortality experience of a cohort of people born in 1970 would require the use of data projection techniques to estimate deaths into the future (3, 4).

The period life table, by contrast, presents what would happen to a hypothetical cohort if it experienced throughout its entire life the mortality conditions of a particular period. For example, a period life table for 2021 assumes a hypothetical cohort that is subject throughout its lifetime to the age-specific death rates prevailing for the actual population in 2021. The period life table could be characterized as producing a snapshot of current mortality experience and showing the long-range implications of a set of age-specific death rates that prevailed in a given year. In this report, the term “life table” refers only to the period life table, not to the cohort life table.

Life tables can be classified in two ways according to the length of the age interval in which data are presented. A complete life table contains data for every single year of age. An abridged life table typically contains data by 5- or 10-year age intervals. A complete life table can be combined into 5- or 10-year age groups. U.S. decennial life tables and, beginning in 1997, U.S. annual life tables are complete life tables. This report presents the results for 2021 in a series of annual, complete period state-specific life tables.

## Data and Methods

The data used to prepare the U.S. state life tables for 2021 are state-specific final numbers of deaths for 2021; July 1, 2021, state-specific population estimates based on the Blended Base produced by the U.S. Census Bureau in lieu of the April 1, 2020, decennial population count. The Blended Base consists of the blend of 2020 postcensal population estimates, based on the April 1, 2010, census; 2020 Demographic Analysis Estimates; and the 2020 Census PL 94-171 Redistricting File (see https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2021/methods-statement-v2021.pdf); and state-specific death and population counts for Medicare beneficiaries ages 66–99 for 2021 from the Centers for Medicare & Medicaid Services. Data from the Medicare program are used to supplement vital statistics and census data for those ages 66 and older.

The methodology used to estimate the 2021 complete life tables for the 50 states and D.C. presented in this report is the same as that used to estimate the annual U.S. national life tables, with some modifications. For some states, very small age-specific or zero numbers of deaths in childhood ages sometimes required the use of additional smoothing techniques not needed in constructing the national life tables. A modification to the estimation of death rates in the oldest ages was also necessary because of the lack of state-specific census population estimates for ages 85–100. The methodology with modifications used to construct the first set of annual U.S. state life tables is detailed in Technical Notes.

### Explanation of life table columns

Column 1. Age (between x and x+1)—Shows the age interval between the two exact ages indicated. For instance, 20–21 means the 1-year interval between the 20th and 21st birthdays.

Column 2. Probability of dying (q_x_)—Shows the probability of dying between ages x and x+1. For example, for males who reach age 20 in Massachusetts, the probability of dying before reaching their 21st birthday is 0.000756 (Table MA–2 (https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/73-07/MA2.xlsx)). This column forms the basis of the life table; all subsequent columns are calculated from it.

Column 3. Number surviving (l_x_)—Shows the number of people from the original hypothetical cohort of 100,000 live births who survive to the beginning of each age interval. The l_x_ values are computed from the q_x_ values, which are successively applied to the remainder of the original 100,000 people still alive at the beginning of each age interval. For example, out of 100,000 male babies born alive in Massachusetts in 2021, 99,196 will survive to their 21st birthday (Table MA–2 (https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/73-07/MA2.xlsx)).

Column 4. Number dying (d_x_)—Shows the number dying in each successive age interval out of the original 100,000 live births. For example, out of 100,000 males born alive in Massachusetts in 2021, 75 will die between ages 20 and 21 (Table MA–2 (https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/73-07/MA2.xlsx)). Each figure in column 4 is the difference between two successive figures in column 3.

Column 5. Person-years lived (L_x_)—Shows the number of person-years lived by the hypothetical life table cohort within an age interval x to x+1. Each figure in column 5 represents the total time (in years) lived between two indicated birthdays by all those reaching the earlier birthday. Consequently, the figure 99,233 for males in the age interval 20–21 is the total number of years lived between the 20th and 21st birthdays by the 99,271 males in Massachusetts (column 3) who reached their 20th birthday out of 100,000 males born alive (Table MA–2 (https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/73-07/MA2.xlsx)).

Column 6. Total number of person-years lived (T_x_)—Shows the total number of person-years that would be lived after the beginning of the age interval x to x+1 by the hypothetical life table cohort. For example, the figure 5,703,533 is the total number of years lived after reaching age 20 by the 99,271 males reaching that age in Massachusetts (Table MA–2 (https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/73-07/MA2.xlsx)).

Column 7. Expectation of life (e_x_)—At any given age, shows the average number of years remaining to be lived by those surviving to that age, based on a given set of age-specific rates of dying. It is calculated by dividing the total person-years that would be lived beyond age x by the number of people who survived to that age interval (T_x_/l_x_). For example, the average remaining lifetime for males in Massachusetts who reach age 20 is 57.5 years (5,703,533 divided by 99,271) (Table MA–2 (https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/73-07/MA2.xlsx)).

### Standard errors of probability of dying and life expectancy

Although based on complete counts of death, the life table functions presented in this report are subject to error. As a result, standard errors of the two most important functions, the probability of dying and life expectancy, are also presented. The mortality data on which state life tables are based are not affected by sampling error because they are based on complete counts of deaths and, as a result, standard errors reflect only stochastic (random) variation. While measurement errors such as age misreporting on death certificates or census data are known to affect mortality estimates, they are not considered in calculating the standard errors of the life table functions. In most cases, standard errors for life expectancy at birth and the probability of dying are small due to large numbers of deaths. However, for some states with small populations, particularly at the youngest ages, the standard errors presented are relatively large.

## Results

### Complete life tables for 50 states and D.C.

A set of complete period life tables for each state and D.C. is available online from “U.S. State Life Tables, 2021” at: ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/73-07/. Table I lists table titles for each of these tables. Table numbering is based on the federal information processing standards, or FIPS, alphabetical code for the state combined with a table code. The table codes are 1 for the total population, 2 for males, 3 for females, and 4 for the standard errors of the probability of dying and life expectancy. For example, Table FL–2 (https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/73-07/FL2.xlsx) refers to the complete period life table for males in Florida.

### Life expectancy in 50 states and D.C.

Table A shows life expectancy at birth for the total, male, and female populations for each state, D.C., and the United States. In 2021, among the 50 states and D.C., Hawaii ranked first for the total, male, and female populations, with life expectancies at birth of 79.9, 77.0, and 83.1 years, respectively. Mississippi ranked 51st among the 50 states and D.C. for the total and male populations, with life expectancies at birth of 70.9 and 67.7, respectively. West Virginia ranked 51st for females with a life expectancy of 74.2. In comparison, life expectancy at birth for the entire United States was 76.4, 73.5, and 79.3 for the total, male, and female populations, respectively. Figure 1 presents a U.S. map with state-specific life expectancy at birth grouped into quartiles. It shows that states with the lowest life expectancy at birth were mostly Southern states (Oklahoma, Louisiana, Mississippi, Alabama, Georgia, South Carolina, Tennessee, Arkansas, Kentucky, and West Virginia) but also included New Mexico, Ohio, and Alaska. States with the highest life expectancy at birth were predominantly Western (Hawaii, California, and Washington) and Northeastern states (New York, Vermont, New Hampshire, Connecticut, Massachusetts, Rhode Island, and New Jersey) but also included Utah and Minnesota.

Table A Life expectancy at birth, rank, and standard error, by sex: Each state, District of Columbia, and United States, 2021

| Total | | | Male | | | Female
Area | Rank | Life expectancy (years) | Standard error | Rank | Life expectancy (years) | Standard error | Rank | Life expectancy (years) | Standard error
Hawaii | 1 | 79.9 | 0.118 | 1 | 77.0 | 0.172 | 1 | 83.1 | 0.155
Massachusetts | 2 | 79.6 | 0.050 | 2 | 76.9 | 0.074 | 2 | 82.2 | 0.065
Connecticut | 3 | 79.2 | 0.074 | 4 | 76.3 | 0.110 | 3 | 82.0 | 0.097
New York | 4 | 79.0 | 0.031 | 7 | 76.3 | 0.045 | 4 | 81.6 | 0.040
New Jersey | 5 | 79.0 | 0.045 | 5 | 76.3 | 0.065 | 5 | 81.6 | 0.058
Minnesota | 6 | 78.8 | 0.059 | 3 | 76.3 | 0.086 | 6 | 81.4 | 0.078
New Hampshire | 7 | 78.5 | 0.117 | 8 | 76.1 | 0.172 | 9 | 81.1 | 0.155
Rhode Island | 8 | 78.5 | 0.130 | 9 | 75.9 | 0.191 | 10 | 81.0 | 0.171
Vermont | 9 | 78.4 | 0.176 | 11 | 75.7 | 0.255 | 8 | 81.2 | 0.237
California | 10 | 78.3 | 0.023 | 13 | 75.3 | 0.033 | 7 | 81.4 | 0.030
Washington | 11 | 78.2 | 0.050 | 10 | 75.8 | 0.073 | 11 | 80.8 | 0.067
Utah | 12 | 78.2 | 0.078 | 6 | 76.3 | 0.113 | 18 | 80.2 | 0.105
Nebraska | 13 | 77.8 | 0.101 | 12 | 75.4 | 0.143 | 16 | 80.3 | 0.138
Wisconsin | 14 | 77.8 | 0.059 | 14 | 75.2 | 0.085 | 14 | 80.5 | 0.079
Colorado | 15 | 77.7 | 0.060 | 16 | 75.0 | 0.087 | 12 | 80.6 | 0.080
Iowa | 16 | 77.7 | 0.077 | 15 | 75.2 | 0.111 | 15 | 80.4 | 0.103
North Dakota | 17 | 77.6 | 0.164 | 17 | 75.0 | 0.232 | 13 | 80.5 | 0.224
Oregon | 18 | 77.4 | 0.067 | 18 | 74.8 | 0.098 | 17 | 80.2 | 0.089
Maryland | 19 | 77.2 | 0.059 | 20 | 74.3 | 0.087 | 20 | 79.9 | 0.077
Idaho | 20 | 77.2 | 0.104 | 19 | 74.8 | 0.151 | 22 | 79.7 | 0.137
Illinois | 21 | 77.1 | 0.041 | 21 | 74.2 | 0.060 | 19 | 80.0 | 0.054
Virginia | 22 | 76.8 | 0.049 | 22 | 74.2 | 0.071 | 24 | 79.4 | 0.065
Maine | 23 | 76.7 | 0.126 | 24 | 73.8 | 0.184 | 21 | 79.8 | 0.166
South Dakota | 24 | 76.6 | 0.164 | 23 | 74.1 | 0.230 | 25 | 79.3 | 0.230
Pennsylvania | 25 | 76.4 | 0.041 | 25 | 73.6 | 0.058 | 26 | 79.3 | 0.054
United States | … | 76.4 | … | … | 73.5 | … | … | 79.3 | …
Delaware | 26 | 76.3 | 0.150 | 27 | 73.3 | 0.218 | 23 | 79.4 | 0.199
Florida | 27 | 76.1 | 0.033 | 28 | 73.1 | 0.048 | 27 | 79.3 | 0.044
Kansas | 28 | 76.0 | 0.086 | 26 | 73.4 | 0.122 | 29 | 78.7 | 0.116
Montana | 29 | 75.8 | 0.145 | 29 | 73.1 | 0.210 | 28 | 78.8 | 0.195
Michigan | 30 | 75.7 | 0.046 | 30 | 72.9 | 0.067 | 30 | 78.6 | 0.062
Texas | 31 | 75.4 | 0.027 | 31 | 72.7 | 0.038 | 33 | 78.3 | 0.036
District of Columbia | 32 | 75.3 | 0.190 | 37 | 71.9 | 0.275 | 31 | 78.5 | 0.258
Nevada | 33 | 75.1 | 0.083 | 33 | 72.4 | 0.119 | 34 | 78.2 | 0.112
Arizona | 34 | 75.0 | 0.057 | 36 | 72.0 | 0.082 | 32 | 78.3 | 0.076
Wyoming | 35 | 75.0 | 0.199 | 32 | 72.5 | 0.281 | 37 | 77.7 | 0.275
North Carolina | 36 | 74.9 | 0.046 | 35 | 72.0 | 0.068 | 35 | 77.9 | 0.061
Missouri | 37 | 74.6 | 0.060 | 40 | 71.6 | 0.088 | 36 | 77.8 | 0.080
Indiana | 38 | 74.6 | 0.057 | 38 | 71.8 | 0.083 | 39 | 77.5 | 0.077
Alaska | 39 | 74.5 | 0.180 | 34 | 72.2 | 0.250 | 40 | 77.3 | 0.256
Ohio | 40 | 74.5 | 0.044 | 39 | 71.7 | 0.063 | 38 | 77.5 | 0.058
Georgia | 41 | 74.3 | 0.045 | 41 | 71.6 | 0.065 | 41 | 77.1 | 0.060
South Carolina | 42 | 73.5 | 0.069 | 42 | 70.4 | 0.100 | 43 | 76.7 | 0.092
New Mexico | 43 | 73.0 | 0.113 | 46 | 69.4 | 0.161 | 42 | 77.0 | 0.152
Oklahoma | 44 | 72.7 | 0.074 | 43 | 70.0 | 0.105 | 45 | 75.6 | 0.103
Arkansas | 45 | 72.5 | 0.089 | 44 | 69.7 | 0.127 | 46 | 75.6 | 0.121
Tennessee | 46 | 72.4 | 0.057 | 47 | 69.4 | 0.083 | 47 | 75.5 | 0.077
Kentucky | 47 | 72.3 | 0.071 | 45 | 69.6 | 0.101 | 49 | 75.3 | 0.096
Louisiana | 48 | 72.2 | 0.073 | 49 | 68.8 | 0.105 | 44 | 75.9 | 0.098
Alabama | 49 | 72.0 | 0.069 | 48 | 68.9 | 0.100 | 48 | 75.3 | 0.091
West Virginia | 50 | 71.0 | 0.117 | 50 | 68.1 | 0.167 | 51 | 74.2 | 0.159
Mississippi | 51 | 70.9 | 0.092 | 51 | 67.7 | 0.133 | 50 | 74.3 | 0.125

… Category not applicable.

NOTE: Life expectancies shown are rounded, but rankings are based on unrounded life expectancies.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 1 Life expectancy at birth: Each state, District of Columbia, and United States, 2021

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 1 is a four-color heat map showing life expectancy at birth for each state, District of Columbia, and the United States in 2021.

The difference in life expectancy between the sexes in the United States was 5.8 years in 2021, ranging from a high of 7.6 years in New Mexico to a low of 3.9 years in Utah (Figure 2). With a few exceptions, the states with the largest differences by sex are those with lower life expectancy at birth, while the smallest sex differences are found mostly among states with higher life expectancy.

Figure 2 Difference between male and female life expectancy at birth: Each state, District of Columbia, and United States, 2021

NOTE: The color key reflects age ranges of life expectancy at birth for the total population for each area.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 2 is a bar chart showing difference between male and female life expectancy at birth for each state, the District of Columbia, and the United States in 2021.

Table B shows life expectancy at age 65 for the total, male, and female populations for the 50 states, D.C., and United States. In 2021, Hawaii ranked first for the total, male, and female populations, with life expectancy at age 65 of 20.6, 18.9, and 22.2 years, respectively. Mississippi ranked 51st, with the lowest life expectancy among the 50 states and D.C. for the total and male populations, with life expectancy at age 65 of 16.1 and 14.6, respectively. West Virginia ranked 51st for females, with life expectancy at age 65 of 17.3 years. In comparison, life expectancy at age 65 for the entire United States was 18.4, 17.0, and 19.7 for the total, male, and female populations, respectively. Figure 3 shows that states with the lowest life expectancies at age 65 are mostly concentrated in the South, with Florida being a noted exception, and those with the highest life expectancies are mostly in the West and Northeast.

Table B Life expectancy at age 65, rank, and standard error, by sex: Each state, District of Columbia, and United States, 2021

| Total | | | Male | | | Female
Area | Rank | Life expectancy (years) | Standard error | Rank | Life expectancy (years) | Standard error | Rank | Life expectancy (years) | Standard error
Hawaii | 1 | 20.6 | 0.064 | 1 | 18.9 | 0.089 | 1 | 22.2 | 0.088
Connecticut | 2 | 19.9 | 0.038 | 2 | 18.4 | 0.053 | 2 | 21.2 | 0.053
Massachusetts | 3 | 19.6 | 0.028 | 4 | 18.1 | 0.039 | 3 | 20.9 | 0.038
Minnesota | 4 | 19.4 | 0.031 | 5 | 18.1 | 0.042 | 5 | 20.7 | 0.043
New York | 5 | 19.4 | 0.017 | 6 | 17.9 | 0.024 | 6 | 20.7 | 0.023
Vermont | 6 | 19.4 | 0.081 | 3 | 18.2 | 0.114 | 10 | 20.5 | 0.114
New Jersey | 7 | 19.4 | 0.025 | 7 | 17.9 | 0.034 | 8 | 20.6 | 0.034
California | 8 | 19.3 | 0.013 | 11 | 17.8 | 0.018 | 4 | 20.7 | 0.018
South Dakota | 9 | 19.2 | 0.077 | 12 | 17.8 | 0.104 | 7 | 20.6 | 0.110
North Dakota | 10 | 19.1 | 0.089 | 14 | 17.6 | 0.119 | 9 | 20.6 | 0.128
Colorado | 11 | 19.1 | 0.031 | 10 | 17.8 | 0.044 | 11 | 20.4 | 0.043
Washington | 12 | 19.1 | 0.027 | 13 | 17.7 | 0.038 | 12 | 20.3 | 0.037
New Hampshire | 13 | 19.0 | 0.057 | 9 | 17.8 | 0.079 | 15 | 20.2 | 0.079
Rhode Island | 14 | 19.0 | 0.067 | 15 | 17.6 | 0.095 | 13 | 20.3 | 0.093
Wisconsin | 15 | 18.9 | 0.029 | 16 | 17.5 | 0.040 | 14 | 20.2 | 0.041
Utah | 16 | 18.8 | 0.046 | 8 | 17.9 | 0.065 | 25 | 19.7 | 0.064
Nebraska | 17 | 18.8 | 0.054 | 21 | 17.2 | 0.074 | 16 | 20.2 | 0.076
Maryland | 18 | 18.7 | 0.030 | 17 | 17.4 | 0.043 | 20 | 19.9 | 0.042
Florida | 19 | 18.7 | 0.016 | 22 | 17.2 | 0.022 | 17 | 20.2 | 0.021
Oregon | 20 | 18.6 | 0.035 | 19 | 17.3 | 0.049 | 21 | 19.9 | 0.048
Delaware | 21 | 18.6 | 0.068 | 25 | 17.1 | 0.096 | 18 | 20.0 | 0.094
Maine | 22 | 18.6 | 0.055 | 18 | 17.3 | 0.077 | 24 | 19.8 | 0.076
Illinois | 23 | 18.6 | 0.021 | 24 | 17.1 | 0.030 | 22 | 19.9 | 0.030
Iowa | 24 | 18.6 | 0.041 | 26 | 17.1 | 0.056 | 19 | 19.9 | 0.059
United States | … | 18.4 | … | … | 17.0 | … | … | 19.7 | …
Idaho | 25 | 18.4 | 0.052 | 20 | 17.2 | 0.073 | 29 | 19.5 | 0.074
Montana | 26 | 18.4 | 0.064 | 23 | 17.1 | 0.088 | 26 | 19.6 | 0.090
New Mexico | 27 | 18.3 | 0.050 | 27 | 16.9 | 0.071 | 27 | 19.6 | 0.070
District of Columbia | 28 | 18.3 | 0.117 | 33 | 16.5 | 0.171 | 23 | 19.8 | 0.157
Virginia | 29 | 18.2 | 0.026 | 28 | 16.9 | 0.036 | 31 | 19.4 | 0.036
Pennsylvania | 30 | 18.2 | 0.020 | 31 | 16.7 | 0.027 | 28 | 19.6 | 0.028
Arizona | 31 | 18.1 | 0.028 | 32 | 16.6 | 0.040 | 30 | 19.5 | 0.038
Kansas | 32 | 18.0 | 0.044 | 34 | 16.5 | 0.061 | 32 | 19.4 | 0.062
Alaska | 33 | 17.9 | 0.087 | 29 | 16.7 | 0.118 | 33 | 19.2 | 0.126
Michigan | 34 | 17.9 | 0.022 | 35 | 16.5 | 0.031 | 34 | 19.1 | 0.031
Wyoming | 35 | 17.8 | 0.091 | 30 | 16.7 | 0.126 | 37 | 18.9 | 0.129
North Carolina | 36 | 17.7 | 0.023 | 36 | 16.3 | 0.032 | 36 | 18.9 | 0.031
Missouri | 37 | 17.6 | 0.029 | 37 | 16.2 | 0.041 | 38 | 18.8 | 0.041
Nevada | 38 | 17.5 | 0.042 | 38 | 16.1 | 0.060 | 35 | 19.0 | 0.059
Texas | 39 | 17.5 | 0.015 | 39 | 16.1 | 0.021 | 40 | 18.7 | 0.021
South Carolina | 40 | 17.4 | 0.031 | 40 | 16.0 | 0.045 | 39 | 18.8 | 0.043
Ohio | 41 | 17.3 | 0.021 | 42 | 15.9 | 0.029 | 41 | 18.6 | 0.029
Indiana | 42 | 17.3 | 0.029 | 41 | 16.0 | 0.039 | 42 | 18.6 | 0.040
Georgia | 43 | 17.1 | 0.023 | 43 | 15.7 | 0.033 | 43 | 18.3 | 0.032
Louisiana | 44 | 16.8 | 0.034 | 44 | 15.3 | 0.048 | 44 | 18.3 | 0.048
Arkansas | 45 | 16.6 | 0.043 | 46 | 15.2 | 0.060 | 45 | 18.1 | 0.059
Tennessee | 46 | 16.6 | 0.028 | 45 | 15.3 | 0.039 | 46 | 17.8 | 0.038
Kentucky | 47 | 16.4 | 0.034 | 47 | 15.1 | 0.047 | 49 | 17.6 | 0.048
Oklahoma | 48 | 16.4 | 0.038 | 48 | 15.0 | 0.052 | 48 | 17.7 | 0.053
Alabama | 49 | 16.4 | 0.032 | 49 | 14.9 | 0.045 | 47 | 17.7 | 0.044
West Virginia | 50 | 16.1 | 0.050 | 50 | 14.8 | 0.070 | 51 | 17.3 | 0.071
Mississippi | 51 | 16.1 | 0.043 | 51 | 14.6 | 0.060 | 50 | 17.5 | 0.060

… Category not applicable.

NOTE: Life expectancies shown are rounded, but rankings are based on unrounded life expectancies.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 3 Life expectancy at age 65: Each state, District of Columbia, and United States, 2021

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 3 is a four-color heat map showing life expectancy at age 65 for each state, the District of Columbia, and the United States in 2021.

From 2020 to 2021, life expectancy at birth declined for 39 states (Table C, Figure 4) (5). The declines ranged from 0.1 to 2.1 years. Life expectancy increased for 11 states, with increases ranging from 0.1 to 1.5 years. The states with the greatest decreases in life expectancy at birth from 2020 to 2021 included Alaska, West Virginia, New Mexico, Florida, Oklahoma, Oregon, and Tennessee. The states that experienced increases in life expectancy included New Jersey, New York, Connecticut, North Dakota, Massachusetts, Maryland, Rhode Island, Illinois, Iowa, Wisconsin, and Nebraska. Life expectancy did not change for D.C. Overall, life expectancy in the United States declined by 0.6 years from 2020 to 2021, mostly due to the COVID-19 pandemic and increases in unintentional injuries (mainly drug overdose deaths) (1).

Table C Change in life expectancy at birth: Each state, District of Columbia, and United States, from 2020 to 2021

Area | 2021 | 2020 | Change in life expectancy from 2020 to 2021
Alaska | 74.5 | 76.6 | -2.1
West Virginia | 71.0 | 72.8 | -1.8
New Mexico | 73.0 | 74.5 | -1.5
Florida | 76.1 | 77.5 | -1.4
Oklahoma | 72.7 | 74.1 | -1.4
Oregon | 77.4 | 78.8 | -1.4
Tennessee | 72.4 | 73.8 | -1.4
Arizona | 75.0 | 76.3 | -1.3
Arkansas | 72.5 | 73.8 | -1.3
Georgia | 74.3 | 75.6 | -1.3
South Carolina | 73.5 | 74.8 | -1.3
Wyoming | 75.0 | 76.3 | -1.3
Alabama | 72.0 | 73.2 | -1.2
Idaho | 77.2 | 78.4 | -1.2
Kentucky | 72.3 | 73.5 | -1.2
Nevada | 75.1 | 76.3 | -1.2
North Carolina | 74.9 | 76.1 | -1.2
Maine | 76.7 | 77.8 | -1.1
Texas | 75.4 | 76.5 | -1.1
Mississippi | 70.9 | 71.9 | -1.0
Montana | 75.8 | 76.8 | -1.0
Washington | 78.2 | 79.2 | -1.0
Louisiana | 72.2 | 73.1 | -0.9
Hawaii | 79.9 | 80.7 | -0.8
Ohio | 74.5 | 75.3 | -0.8
Virginia | 76.8 | 77.6 | -0.8
California | 78.3 | 79.0 | -0.7
Colorado | 77.7 | 78.3 | -0.6
United States | 76.4 | 77.0 | -0.6
Missouri | 74.6 | 75.1 | -0.5
New Hampshire | 78.5 | 79.0 | -0.5
Delaware | 76.3 | 76.7 | -0.4
Indiana | 74.6 | 75.0 | -0.4
Kansas | 76.0 | 76.4 | -0.4
Pennsylvania | 76.4 | 76.8 | -0.4
Utah | 78.2 | 78.6 | -0.4
Vermont | 78.4 | 78.8 | -0.4
Michigan | 75.7 | 76.0 | -0.3
Minnesota | 78.8 | 79.1 | -0.3
South Dakota | 76.6 | 76.7 | -0.1
District of Columbia | 75.3 | 75.3 | 0.0
Nebraska | 77.8 | 77.7 | 0.1
Wisconsin | 77.8 | 77.7 | 0.1
Iowa | 77.7 | 77.5 | 0.2
Illinois | 77.1 | 76.8 | 0.3
Rhode Island | 78.5 | 78.2 | 0.3
Maryland | 77.2 | 76.8 | 0.4
Massachusetts | 79.6 | 79.0 | 0.6
North Dakota | 77.6 | 76.9 | 0.7
Connecticut | 79.2 | 78.4 | 0.8
New York | 79.0 | 77.7 | 1.3
New Jersey | 79.0 | 77.5 | 1.5

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 4 Change in life expectancy at birth from 2020 to 2021: Each state, District of Columbia, and United States, 2021

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 4 is a four-color heat map showing change in life expectancy at birth from 2020 to 2021 for each state, the District of Columbia, and the United States in 2021.

## Acknowledgments

The authors are grateful for the reviews and comments provided by Robert N. Anderson, Chief, Statistical Analysis and Surveillance Branch, Division of Vital Statistics; Andrés A. Berruti, Associate Director for Science, Division of Vital Statistics; and Amy M. Branum, Associate Director for Science, Office of the Director. The authors thank Anne Driscoll, Danielle Ely, and Brady Hamilton of the Statistical Analysis and Surveillance Branch for their assistance with birth data. The National Center for Health Statistics Office of Information Services, Information Design and Publishing Staff edited and produced this report: editor Laura Drescher and typesetter and graphic designer Erik L. Richardson (contractor).

## References

1 Arias E, Xu JQ, Kochanek K. United States life tables, 2021. National Vital Statistics Reports; vol 72 no 12. Hyattsville, MD: National Center for Health Statistics. 2023. DOI: 10.15620/cdc:132418.
2 Shryock HS, Siegel JS, Larmon EA. The methods and materials of demography, vol 2. Washington, DC: U.S. Census Bureau. 1971.
3 Moriyama IM, Gustavus SO. Cohort mortality and survivorship: United States death-registration states, 1900–1968. National Center for Health Statistics. Vital Health Stat 3(16). 1972. Available from: https://www.cdc.gov/nchs/data/series/sr_03/sr03_016.pdf.
4 Preston SH, Heuveline P, Guillot M. Demography: Measuring and modeling population processes. Oxford, England: Blackwell Publishers. 2001.
5 Arias E, Xu JQ, Tejada-Vera B, Murphy SL, Bastian B. U.S. state life tables, 2020. National Vital Statistics Reports; vol 71 no 2. Hyattsville, MD: National Center for Health Statistics. 2022. DOI: 10.15620/cdc:118271.
6 Bell FC, Miller ML. Life tables for the United States Social Security area 1900–2100. Actuarial Study No. 120. SSA Pub. No. 11–11536. Baltimore, MD: Social Security Administration. 2005.
7 Anderson RN. Method for constructing complete annual U.S. life tables. National Center for Health Statistics. Vital Health Stat 2(129). 1999. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_129.pdf.
8 Thatcher AR, Kannisto V, Vaupel JW. The force of mortality at ages 80 to 120. Odense, Denmark: Odense University Press. 1998.
9 Andreev KF, Bourbeau RR. Frailty modeling of Canadian and Swedish mortality at adult and advanced ages. In: Population Association of America Annual Meeting program. 2007.
10 Chiang CL. The life table and its applications. Malabar, FL: Robert E. Krieger Publishing Company, Inc. 1984.
11 Arias E, Curtin SC, Tejada-Vera B. U.S.decennial life tables for 2009–2011: Methodology of the United States life tables. National Vital Statistics Reports; vol 69 no 10. Hyattsville, MD: National Center for Health Statistics. 2020.
12 Silcocks PB, Jenner DA, Reza R. Life expectancy as a summary of mortality in a population: Statistical considerations and suitability for use by health authorities. J Epidemiol Community Health 55(1): 38–43. 2001.

## Technical Notes

The methods used to estimate the 2021 complete life tables for the 50 states and District of Columbia (D.C.) are the same as those used to estimate the U.S. annual life tables, with two modifications (1) . First, for states with zero death counts at single ages 1–4 years, linear interpolation was used to replace those zero death counts. For a few states, linear interpolation was also used to replace zero and negative death counts resulting from application of the Beers’ smoothing technique to very small death counts for ages 6–12 years. Second, a modification was made to the estimation of the age-specific death rates for ages 66–99. Because state age-specific census population estimates for ages 85–100 are not available, the age range needed to be modified where vital and Medicare death rates are blended and where Medicare data are used exclusively. Details of the methodology and modifications follow.

### Data for calculating life table functions

The data used to prepare the U.S. state life tables (Table I) include state-specific final death counts from the National Vital Statistics System, state-specific population estimates from the U.S. Census Bureau, and state-specific death and population counts for Medicare beneficiaries ages 66–99 from the Centers for Medicare & Medicaid Services.

Table I Complete period life tables: 50 states and District of Columbia, 2021

Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Publications/NVSR/73-07/

Table title
AK–1. | Life table for total population: Alaska, 2021
AK–2. | Life table for males: Alaska, 2021
AK–3. | Life table for females: Alaska, 2021
AK–4. | Standard errors of probability of dying and life expectancy: Alaska, 2021
AL–1. | Life table for total population: Alabama, 2021
AL–2. | Life table for males: Alabama, 2021
AL–3. | Life table for females: Alabama, 2021
AL–4. | Standard errors of probability of dying and life expectancy: Alabama, 2021
AR–1. | Life table for total population: Arkansas, 2021
AR–2. | Life table for males: Arkansas, 2021
AR–3. | Life table for females: Arkansas, 2021
AR–4. | Standard errors of probability of dying and life expectancy: Arkansas, 2021
AZ–1. | Life table for total population: Arizona, 2021
AZ–2. | Life table for males: Arizona, 2021
AZ–3. | Life table for females: Arizona, 2021
AZ–4. | Standard errors of probability of dying and life expectancy: Arizona, 2021
CA–1. | Life table for total population: California, 2021
CA–2. | Life table for males: California, 2021
CA–3. | Life table for females: California, 2021
CA–4. | Standard errors of probability of dying and life expectancy: California, 2021
CO–1. | Life table for total population: Colorado, 2021
CO–2. | Life table for males: Colorado, 2021
CO–3. | Life table for females: Colorado, 2021
CO–4. | Standard errors of probability of dying and life expectancy: Colorado, 2021
CT–1. | Life table for total population: Connecticut, 2021
CT–2. | Life table for males: Connecticut, 2021
CT–3. | Life table for females: Connecticut, 2021
CT–4. | Standard errors of probability of dying and life expectancy: Connecticut, 2021
DC–1. | Life table for total population: District of Columbia, 2021
DC–2. | Life table for males: District of Columbia, 2021
DC–3. | Life table for females: District of Columbia, 2021
DC–4. | Standard errors of probability of dying and life expectancy: District of Columbia, 2021
DE–1. | Life table for total population: Delaware, 2021
DE–2. | Life table for males: Delaware, 2021
DE–3. | Life table for females: Delaware, 2021
DE–4. | Standard errors of probability of dying and life expectancy: Delaware, 2021
FL–1. | Life table for total population: Florida, 2021
FL–2. | Life table for males: Florida, 2021
FL–3. | Life table for females: Florida, 2021
FL–4. | Standard errors of probability of dying and life expectancy: Florida, 2021
GA–1. | Life table for total population: Georgia, 2021
GA–2. | Life table for males: Georgia, 2021
GA–3. | Life table for females: Georgia, 2021
GA–4. | Standard errors of probability of dying and life expectancy: Georgia, 2021
HI–1. | Life table for total population: Hawaii, 2021
HI–2. | Life table for males: Hawaii, 2021
HI–3. | Life table for females: Hawaii, 2021
HI–4. | Standard errors of probability of dying and life expectancy: Hawaii, 2021
IA–1. | Life table for total population: Iowa, 2021
IA–2. | Life table for males: Iowa, 2021
IA–3. | Life table for females: Iowa, 2021
IA–4. | Standard errors of probability of dying and life expectancy: Iowa, 2021
ID–1. | Life table for total population: Idaho, 2021
ID–2. | Life table for males: Idaho, 2021
ID–3. | Life table for females: Idaho, 2021
ID–4. | Standard errors of probability of dying and life expectancy: Idaho, 2021
IL–1. | Life table for total population: Illinois, 2021
IL–2. | Life table for males: Illinois, 2021
IL–3. | Life table for females: Illinois, 2021
IL–4. | Standard errors of probability of dying and life expectancy: Illinois, 2021
IN–1. | Life table for total population: Indiana, 2021
IN–2. | Life table for males: Indiana, 2021
IN–3. | Life table for females: Indiana, 2021
IN–4. | Standard errors of probability of dying and life expectancy: Indiana, 2021
KS–1. | Life table for total population: Kansas, 2021
KS–2. | Life table for males: Kansas, 2021
KS–3. | Life table for females: Kansas, 2021
KS–4. | Standard errors of probability of dying and life expectancy: Kansas, 2021
KY–1. | Life table for total population: Kentucky, 2021
KY–2. | Life table for males: Kentucky, 2021
KY–3. | Life table for females: Kentucky, 2021
KY–4. | Standard errors of probability of dying and life expectancy: Kentucky, 2021
LA–1. | Life table for total population: Louisiana, 2021
LA–2. | Life table for males: Louisiana, 2021
LA–3. | Life table for females: Louisiana, 2021
LA–4. | Standard errors of probability of dying and life expectancy: Louisiana, 2021
MA–1. | Life table for total population: Massachusetts, 2021
MA–2. | Life table for males: Massachusetts, 2021
MA–3. | Life table for females: Massachusetts, 2021
MA–4. | Standard errors of probability of dying and life expectancy: Massachusetts, 2021
MD–1. | Life table for total population: Maryland, 2021
MD–2. | Life table for males: Maryland, 2021
MD–3. | Life table for females: Maryland, 2021
MD–4. | Standard errors of probability of dying and life expectancy: Maryland, 2021
ME–1. | Life table for total population: Maine, 2021
ME–2. | Life table for males: Maine, 2021
ME–3. | Life table for females: Maine, 2021
ME–4. | Standard errors of probability of dying and life expectancy: Maine, 2021
MI–1. | Life table for total population: Michigan, 2021
MI–2. | Life table for males: Michigan, 2021
MI–3. | Life table for females: Michigan, 2021
MI–4. | Standard errors of probability of dying and life expectancy: Michigan, 2021
MN–1. | Life table for total population: Minnesota, 2021
MN–2. | Life table for males: Minnesota, 2021
MN–3. | Life table for females: Minnesota, 2021
MN–4. | Standard errors of probability of dying and life expectancy: Minnesota, 2021
MO–1. | Life table for total population: Missouri, 2021
MO–2. | Life table for males: Missouri, 2021
MO–3. | Life table for females: Missouri, 2021
MO–4. | Standard errors of probability of dying and life expectancy: Missouri, 2021
MS–1. | Life table for total population: Mississippi, 2021
MS–2. | Life table for males: Mississippi, 2021
MS–3. | Life table for females: Mississippi, 2021
MS–4. | Standard errors of probability of dying and life expectancy: Mississippi, 2021
MT–1. | Life table for total population: Montana, 2021
MT–2. | Life table for males: Montana, 2021
MT–3. | Life table for females: Montana, 2021
MT–4. | Standard errors of probability of dying and life expectancy: Montana, 2021
NC–1. | Life table for total population: North Carolina, 2021
NC–2. | Life table for males: North Carolina, 2021
NC–3. | Life table for females: North Carolina, 2021
NC–4. | Standard errors of probability of dying and life expectancy: North Carolina, 2021
ND–1. | Life table for total population: North Dakota, 2021
ND–2. | Life table for males: North Dakota, 2021
ND–3. | Life table for females: North Dakota, 2021
ND–4. | Standard errors of probability of dying and life expectancy: North Dakota, 2021
NE–1. | Life table for total population: Nebraska, 2021
NE–2. | Life table for males: Nebraska, 2021
NE–3. | Life table for females: Nebraska, 2021
NE–4. | Standard errors of probability of dying and life expectancy: Nebraska, 2021
NH–1. | Life table for total population: New Hampshire, 2021
NH–2. | Life table for males: New Hampshire, 2021
NH–3. | Life table for females: New Hampshire, 2021
NH–4. | Standard errors of probability of dying and life expectancy: New Hampshire, 2021
NJ–1. | Life table for total population: New Jersey, 2021
NJ–2. | Life table for males: New Jersey, 2021
NJ–3. | Life table for females: New Jersey, 2021
NJ–4. | Standard errors of probability of dying and life expectancy: New Jersey, 2021
NM–1. | Life table for total population: New Mexico, 2021
NM–2. | Life table for males: New Mexico, 2021
NM–3. | Life table for females: New Mexico, 2021
NM–4. | Standard errors of probability of dying and life expectancy: New Mexico, 2021
NV–1. | Life table for total population: Nevada, 2021
NV–2. | Life table for males: Nevada, 2021
NV–3. | Life table for females: Nevada, 2021
NV–4. | Standard errors of probability of dying and life expectancy: Nevada, 2021
NY–1. | Life table for total population: New York, 2021
NY–2. | Life table for males: New York, 2021
NY–3. | Life table for females: New York, 2021
NY–4. | Standard errors of probability of dying and life expectancy: New York, 2021
OH–1. | Life table for total population: Ohio, 2021
OH–2. | Life table for males: Ohio, 2021
OH–3. | Life table for females: Ohio, 2021
OH–4. | Standard errors of probability of dying and life expectancy: Ohio, 2021
OK–1. | Life table for total population: Oklahoma, 2021
OK–2. | Life table for males: Oklahoma, 2021
OK–3. | Life table for females: Oklahoma, 2021
OK–4. | Standard errors of probability of dying and life expectancy: Oklahoma, 2021
OR–1. | Life table for total population: Oregon, 2021
OR–2. | Life table for males: Oregon, 2021
OR–3. | Life table for females: Oregon, 2021
OR–4. | Standard errors of probability of dying and life expectancy: Oregon, 2021
PA–1. | Life table for total population: Pennsylvania, 2021
PA–2. | Life table for males: Pennsylvania, 2021
PA–3. | Life table for females: Pennsylvania, 2021
PA–4. | Standard errors of probability of dying and life expectancy: Pennsylvania, 2021
RI–1. | Life table for total population: Rhode Island, 2021
RI–2. | Life table for males: Rhode Island, 2021
RI–3. | Life table for females: Rhode Island, 2021
RI–4. | Standard errors of probability of dying and life expectancy: Rhode Island, 2021
SC–1. | Life table for total population: South Carolina, 2021
SC–2. | Life table for males: South Carolina, 2021
SC–3. | Life table for females: South Carolina, 2021
SC–4. | Standard errors of probability of dying and life expectancy: South Carolina, 2021
SD–1. | Life table for total population: South Dakota, 2021
SD–2. | Life table for males: South Dakota, 2021
SD–3. | Life table for females: South Dakota, 2021
SD–4. | Standard errors of probability of dying and life expectancy: South Dakota, 2021
TN–1. | Life table for total population: Tennessee, 2021
TN–2. | Life table for males: Tennessee, 2021
TN–3. | Life table for females: Tennessee, 2021
TN–4. | Standard errors of probability of dying and life expectancy: Tennessee, 2021
TX–1. | Life table for total population: Texas, 2021
TX–2. | Life table for males: Texas, 2021
TX–3. | Life table for females: Texas, 2021
TX–4. | Standard errors of probability of dying and life expectancy: Texas, 2021
UT–1. | Life table for total population: Utah, 2021
UT–2. | Life table for males: Utah, 2021
UT–3. | Life table for females: Utah, 2021
UT–4. | Standard errors of probability of dying and life expectancy: Utah, 2021
VA–1. | Life table for total population: Virginia, 2021
VA–2. | Life table for males: Virginia, 2021
VA–3. | Life table for females: Virginia, 2021
VA–4. | Standard errors of probability of dying and life expectancy: Virginia, 2021
VT–1. | Life table for total population: Vermont, 2021
VT–2. | Life table for males: Vermont, 2021
VT–3. | Life table for females: Vermont, 2021
VT–4. | Standard errors of probability of dying and life expectancy: Vermont, 2021
WA–1. | Life table for total population: Washington, 2021
WA–2. | Life table for males: Washington, 2021
WA–3. | Life table for females: Washington, 2021
WA–4. | Standard errors of probability of dying and life expectancy: Washington, 2021
WI–1. | Life table for total population: Wisconsin, 2021
WI–2. | Life table for males: Wisconsin, 2021
WI–3. | Life table for females: Wisconsin, 2021
WI–4. | Standard errors of probability of dying and life expectancy: Wisconsin, 2021
WV–1. | Life table for total population: West Virginia, 2021
WV–2. | Life table for males: West Virginia, 2021
WV–3. | Life table for females: West Virginia, 2021
WV–4. | Standard errors of probability of dying and life expectancy: West Virginia, 2021
WY–1. | Life table for total population: Wyoming, 2021
WY–2. | Life table for males: Wyoming, 2021
WY–3. | Life table for females: Wyoming, 2021
WY–4. | Standard errors of probability of dying and life expectancy: Wyoming, 2021

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

#### Vital statistics data

Death counts used for computing the life tables presented in this report are state-specific final numbers of deaths for 2021 collected from death certificates filed in state vital statistics offices and reported to the National Center for Health Statistics as part of the National Vital Statistics System.

#### Census population data

The population data used to estimate the life tables shown in this report are postcensal population estimates based on the Blended Base created by the U.S. Census Bureau to produce post-2020 census population estimates. The Blended Base consists of the blend of Vintage 2020 postcensal population estimates, based on the April 1, 2010, decennial census; the 2020 Demographic Analysis Estimates; and the 2020 Census PL 94-171 Redistricting File (see https://www2.census.gov/programs-surveys/popest/technical-documentation/methodology/2020-2021/methods-statement-v2021.pdf).

#### Medicare data

Data from the Medicare program are used to supplement vital statistics and census data for ages 66–99 for the total population and by sex for each state and D.C.

Medicare data are considered more accurate than vital statistics and census data at the oldest ages because Medicare enrollees must have proof of age to enroll (6). However, the reliability of Medicare data beyond age 100 declines because of the small percentage of people who enrolled at the start of the Medicare program in 1965 for whom it was not possible to verify exact age (6) .

To estimate death rates for the state-specific Medicare populations in 2021, sex- and age-specific numbers of deaths and population counts were used for the population ages 66–99 in each state and D.C. from the 2021 Medicare file. The data file, created by the Centers for Medicare & Medicaid Services for the Social Security Administration, is shared with the National Center for Health Statistics under a special agreement. The 2021 file contains state-specific 2021 midyear Medicare population counts (as of June 30, 2021) and calendar-year Medicare death counts (for January 1 through December 31, 2021). Age for both death and midyear population counts is calculated as age at last birthday.

### Preliminary adjustment of data

#### Adjustments for unknown age

An adjustment is made to account for the small proportion of deaths each year for which age is not reported on the death certificate. The number of deaths in each age category is adjusted proportionally to account for those with not-stated age. An adjustment factor (F) is used to distribute deaths with nonstated ages. F is calculated for the total population and by sex for each state and D.C. as:

F = (D)/(D^a^) [1]

where D is the total number of deaths and D^a^ is the total number of deaths for which age is stated. F is then applied by multiplying it by the number of deaths in each age group.

#### Interpolation of P_x_ and D_x_

Anomalies—both random and those associated with reporting age at death—can be problematic when using vital statistics and census data by single years of age to estimate the probability of death (2, 7). Graduation techniques are often used to eliminate these anomalies and to derive a smooth curve by age. Beers’ ordinary minimized fifth difference formula is used to obtain smoothed values of population counts (P_x_) and death counts (D_x_) from 5-year age groupings of _n_P_x_ from ages 0–99 and _n_D_x_ from ages 5–99, and where _n_ D_x_ has first been adjusted for not-reported age on the death certificate (see reference 8 for details on the application of Beers’ method). Beers’ interpolation is not applied to deaths at ages 0–4.

For states with zero death counts in the age range 1–4 years, those counts needed to be replaced using linear interpolation; otherwise, zero death counts would have resulted in discontinuation of the age-specific mortality distribution. In a few other cases, application of Beers’ interpolation of deaths in the age range 6–10 resulted in zero or negative death counts because of very small numbers of deaths, so linear interpolation was also applied. The assumption of linearity is warranted because mortality declines somewhat linearly between ages 1 and 10 or so, and the results led to smooth age patterns of mortality (see Table II for a list of states and ages where linear interpolation was used).

Table II Application of linear interpolation by area, sex, and age

| Age (years)
Area | Male | Female
Alaska | … | 9,10
Connecticut | … | 2,7
Delaware | … | 4
District of Columbia | 2 | 1–4
Hawaii | 3 | 3,4
Maine | … | 2
Montana | 3 | 2,4
New Hampshire | … | 2,3
North Dakota | … | 1,3,4
Oregon | … | 3
Rhode Island | 3,4 | 2–4
Vermont | 2–4,6 | 2,3
West Virginia | 2 | …
Wyoming | 3 | 3,4

… Category not applicable.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

#### Calculation of probability of dying (q_x_)

The first step in the calculation of a complete period life table is estimation of the age-specific probability of dying, q_x_, which is derived from the age-specific death rate, m_x_ (2,4). In the life table cohort,

m_x_ = (d_x_)/(L_x_)

where d_x_ is the number of deaths occurring between ages x and x+1, and L_x_ is the number of person-years lived by the life table cohort between ages x and x + 1. The conversion of the age-specific death rate, m_x_, to the age-specific probability of death, q_x_, is:

q_x_ = (m_x_)/(1 + (1 − a_x_) m_x_) [2]

where a_x_ is the fraction of the number of person-years lived in the age interval by members of the life table cohort who died in the interval. When the age interval is 1 year, except at infancy, a_x_=1/2; in other words, deaths occur on average midway through the age interval. As a result,

q_x_ = (m_x_)/(1 + (1)/(2) m_x_) [3]

Because the complete period life table is based on the age-specific death rates of a current population observed for a specific calendar year, the life table death rate is equivalent to the observed death rate of the current population:

m_x_ = (d_x_)/(L_x_) = M_x_ = (D_x_)/(P_x_)

where D_x_ is the Beers’ smoothed (or linearly interpolated) number of deaths adjusted for not-stated age, and P_x_ is the Beers’ smoothed population at risk of dying between ages x and x+1. Then,

q_x_ = (M_x_)/(1 + (1)/(2) M_x_) = (D_x_)/(P_x_ + (1)/(2) D_x_) [4]

This procedure is used to estimate vital statistics age-specific probabilities of death for ages 1–84.

#### Calculation of q_x_ at age 0

The higher mortality observed in infancy is associated with a high concentration of deaths occurring at the beginning of the age interval rather than in the middle. Consequently, assigning deaths to the appropriate birth cohorts is best whenever possible. As a result, the probability of death at birth, q_0_, is calculated using a birth cohort method that uses a separation factor (f) defined as the proportion of infant deaths in year t occurring to infants born in the previous year (t – 1). The value f is estimated by categorizing infant deaths by date of birth. The probability of death is then calculated as:

q_0_ = (D_0_ (1 − f))/(B^t^) + (D_0_ (f))/(B^t − 1^) [5]

where D_0_ is the number of infant deaths adjusted for not-stated age in 2021, B^t^ is the number of live births in 2021, and B^t– 1^ is the number of live births in 2020.

### Probabilities of dying at oldest ages

Medicare data are used to supplement vital statistics data for the estimation of q_x_ at the oldest ages because these data are more accurate, given that proof of age is required for enrollment in the Medicare program. Medicare data are used here to estimate the probability of dying for ages 66–99.

For this method, these steps are followed: First, vital statistics and Medicare death rates are blended in the age range 66–99. Second, a logistic model is used to smooth the blended death rates in the age range 85–99 and to predict death rates for ages 100–120. Third, final resulting death rates, M_x_, are converted to probabilities of dying, q_x_ .

For the national life tables, vital statistics, M_x_^V^ , and Medicare, M_x_^M^ , death rates are blended in the age range 66–94 with a weighting process that gives gradually declining weight to vital statistics data and gradually increasing weight to Medicare data. For ages 95–99, M_x_^M^ is used exclusively. Due to the unavailability of census state population estimates for ages 85–100, calculating M_x_^V^ for this age span is not possible. As a result, the blending technique was modified such that M_x_^V^ and M_x_^M^ are blended in the age range 66–84, and M_x_^M^ is used exclusively in the age range 85–99. Blended M_x_ is obtained as:

M_x_ = (1)/(20) [(85 − x) M_x_^V^ + (x − 65) M_x_^M^] [6]

when x=66,…,84, and M_x_ = M_x_^M^

when x = 85,…,99.

M_x_^M^ is estimated as:

M_x_^M^ = (D_x_^M^)/(P_x_^M^)

where D_x_^M^ is the age-specific Medicare death count, and P_x_^M^ is the age-specific Medicare midyear population count.

The exclusive use of Medicare death rates beginning at age 85 for the state life tables is expected to have a negligible biasing effect on mortality at older ages in the life tables compared with the national life tables. As Figures I–III show, while large differences are found between Medicare and vital statistics death rates at ages 85 and older for the U.S. population, blended Medicare and vital statistics death rates are very similar to Medicare death rates for ages 85 and older.

Figure I Age-specific vital statistics, Medicare, and blended death rates for total population: United States, 2021

^1^Rate (M_x_) is defined as the number of deaths during the year divided by the midyear population (D_x_/P_x_).

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure I is a line chart showing age-specific vital statistics, Medicare, and blended death rates for the total population in the United States in 2021.

Figure II Age-specific vital statistics, Medicare, and blended death rates for male population: United States, 2021

^1^Rate (M_x_) is defined as the number of deaths during the year divided by the midyear population (D_x_/P_x_).

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure II is a line chart showing age-specific vital statistics, Medicare, and blended death rates for the male population in the United States in 2021.

Figure III Age-specific vital statistics, Medicare, and blended death rates for female population: United States, 2021

^1^Rate (M_x_) is defined as the number of deaths during the year divided by the midyear population (D_x_/P_x_).

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure III is a line chart showing age-specific vital statistics, Medicare, and blended death rates for the female population in the United States in 2021.

A logistic model proposed by Kannisto is then used to smooth M_x_ in the age range 85–99 and to predict M_x_ in the age range 100–120 (8). The start of the modeled age range varies by sex because it is a function of the age at which the rate of change in the age-specific death rates peaks. In current times, the rate of change in the age-specific death rate rises steadily up to about ages 80–85 and then begins to decline. As a result, modeling a large age span such as 65–100 with one simple model is difficult without oversmoothing and consequently altering the underlying mortality pattern observed in the population of interest (9). Further, the observed data for the age range 65–85 or so is reliable and robust, as indicated by the very close similarity between vital statistics and Medicare death rates, making it unnecessary to model, or smooth, the entire age span (65–100).

The Kannisto model is a simple form of a logistic model in which the logit of u_x_ (or the natural log of the odds of u_x_) is a linear function of age x ({8}). It is expressed as:

ln [(u_x_)/(1 − u_x_)] = ln (α) + β x [7]

where u_x_, the force of mortality (or the instantaneous death rate) is defined as:

u_x_ = (α e^β x^)/(1 + α e^β x^)

Because u_x_ is not directly observed but is closely approximated by m_x_, and m_x_=M_ x_, then the logit of M_x_ is modeled instead. A maximum-likelihood generalized linear model estimation procedure is used to fit the following model in the age range 85–99:

ln [(M_x_)/(1 − M_x_)] = ln (α) + β x [8]

Then, the estimated parameters are used to predict M¯_x_ as:

M¯_x_ = (e^a^ e^b x^)/(1 + e^a^ e^b x^) or, equivalently, M¯_x_ = (e^a + b x^)/(1 + e^a + b x^) [9]

where a and b are the predicted values of parameters ln(α) and β, respectively, given by fitting model 8.

Finally, the predicted probability of death, q¯_x_ , for ages 85–120 is estimated by converting M¯_x_ as:

q¯_x_ = (M¯_x_)/(1 + (1)/(2) M¯_x_) [10]

The probability of death is extrapolated to age 120 to estimate the life table population until no survivors remain. This information is then used to estimate L_x_ for ages 100–120, which is used to close the table with the age category 100 and older, combined (see following discussion).

Figures IV–VI show the age-specific probability of dying, q_x_, estimates for each of the 50 states and D.C. compared with the values for the United States in 2021. The observed probabilities for the states and D.C. are shown as circles, which appear as vertical bars where they overlap, and the U.S. probabilities are shown as an intersecting connected line. The state estimates fall about the U.S. values as expected, with a few outliers in the youngest childhood ages. These few cases are predominantly the result of a very small number of deaths, consistent with very low mortality in this age range, combined with very small populations in states such as Vermont, Wyoming, and North Dakota. Overall, age-specific estimates for the 50 states and D.C. follow the expected age pattern of mortality and are consistent with the mortality pattern observed for the entire United States.

Figure IV Age patterns of mortality for states and District of Columbia compared with United States, 2021

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure IV is a combined line and scatter chart showing the age patterns of mortality for states and the District of Columbia compared with the United States in 2021.

Figure V Male age patterns of mortality for states and District of Columbia compared with United States, 2021

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure V is a combined line and scatter chart showing male age patterns of mortality for states and the District of Columbia compared with the United States in 2021.

Figure VI Female age patterns of mortality for states and District of Columbia compared with United States, 2021

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure VI is a combined line and scatter chart showing female age patterns of mortality for states and the District of Columbia compared with the United States in 2021.

### Calculation of remaining life table functions for all groups

#### Survivor function (l_x_)

The life table radix, l_0_, is set at 100,000. For ages older than 0, the number of survivors remaining at exact age x is calculated as:

l_x_ = l_x − 1_ (1 − q_x − 1_) [11]

#### Decrement function (d_x_)

The number of deaths occurring between ages x and x+1 is calculated from the survivor function:

d_x_ = l_x_ − l_x + 1_ = l_x_ q_x_ [12]

Note that _∞_d_100_ = _∞_I_100_ because _∞_q_100_ = 1.0 .

#### Person-years lived (L_x_)

Person-years lived for ages 1–99 are calculated assuming that the survivor function declines linearly between ages x and x+1. This gives the formula:

L_x_ = (1)/(2) (l_x_ + l_x + 1_) = l_x_ − (1)/(2) d_x_ [13]

For x=0, the separation factor f is used to calculate L_0_ :

L_0_ = f l_0_ + (1 − f) l_1_ [14]

Finally, _∞_L_100_ is estimated as the sum of the extrapolated L_x_ values for ages 100–120.

#### Person-years lived at age x and older (T_x_)

T_x_ is calculated by summing L_x_ values at age x and older:

T_x_ = ∑_x = 0_^∞^ L_x_ [15]

#### Life expectancy at age x (e_x_)

Life expectancy at exact age x is calculated as:

e_x_ = (T_x_)/(l_x_) [16]

### Variances and standard errors of probability of dying and life expectancy

The mortality data on which the life tables are based are not affected by sampling error because the data are based on complete counts of deaths, and, as a result, variances and standard errors reflect only random variation. While measurement errors such as age misreporting are known to affect mortality estimates, they are not considered in the calculation of the variances or standard errors of the life table functions. Because the state life tables presented in this report are based on relatively large numbers of deaths, the variances and standard errors presented are rather small.

The methods used to estimate the variances of q_x_ and e_x_ are based on Chiang (10) with some necessary modifications due to the use of statistical modeling for smoothing and prediction of older-age death rates. Based on the assumption that deaths are binomially distributed, Chiang proposed the following equation for the variance of q_x_ :

V a r (q_x_) = (q_x_^2^ (1 − q_x_))/(D_x_) [17]

where D_x_ is the age-specific death count. This equation is used to estimate Var (q_x_) throughout the age span with a modification where, for ages younger than age 66, D_x_ is the deaths from vital statistics data, smoothed by interpolation and adjusted for the number of deaths with age not stated. For ages 66 and older, D_x_ is obtained by treating the population as a cohort population and calculated from q_x_ because blended vital statistics and Medicare data were used for estimation (11):

P_x_ = (( P_x − 1_ − 0.5 D_x − 1_ ) (2 − q_x_))/(2)

D_x_ = (q_x_ P_x_)/(1 − 0.5 q_x_)

#### Standard error of q_x_

The standard error of q_x_ is calculated as:

S E (q_x_) = sqrt(V a r (q_x_)) [18]

Variances of the life expectancies for ages 0–99 are estimated using Chiang’s equation:

V a r (e_x_) = (∑_x = 0_^x = 99^ l_x_^2^ • [(1 − 0.5) + e_x_]^2^ • V a r (q_x_))/(l_x_^2^) [19]

Chiang assumed that because q_100+_ =1.00, then Var (q_100+_)=0, and as a result, Var (e_100+_)=0. Silcocks et al. proposed that in the final age group, life expectancy is dependent on the mean length of survival and not on the probability of survival, and consequently the assumption of no variance is incorrect. Var (e_100+_) can be approximated as (12):

V a r (e_100 +_) ≈ [(l_100 +_^2^)/(M_100 +_^4^) • V a r (M_100 +_)] / l_100 +_^2^ [20]

#### Standard error of e_x_

The standard error of e_x_ is calculated as:

S E (e_x_) = sqrt(V a r ( e_x_ )) [21]

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Vital Statistics

Paul D. Sutton, Ph.D., Acting Director

Andrés A. Berruti, Ph.D., M.A., Associate Director for Science

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/email-updates.htm.

For questions or general information about NCHS: Tel: 1–800–CDC–INFO (1–800–232–4636) • TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs • Online request form: https://www.cdc.gov/info • CS350476