# Report No. 221 Fatigue Among Adults Age 18 and Older: United States, 2024

### Objective

This report describes fatigue symptoms among adults by sociodemographic characteristics, as well as co-occurrence with functioning difficulties and limitations in work and social activities.

### Methods

Data from the 2024 National Health Interview Survey were used to estimate fatigue symptoms among adults age 18 and older. Fatigue is based on reported frequency of fatigue in the past 3 months, with frequent fatigue defined as experiencing fatigue symptoms most days or every day during the 3-month period. Estimates are presented by sex, age, race and Hispanic origin, family income, region, and urbanization. Measures of functioning difficulties include seeing, hearing, walking, communication, cognition, self-care, upper body, anxiety, and depression. Measures of participation limitations in work and social activities are also described.

### Results

In 2024, 71.5% of adults reported experiencing fatigue at least some days in the past 3 months (54.9% some days, 10.7% most days, and 5.9% every day), with frequent fatigue reported by 16.6% of adults. Frequent fatigue was more common among women (20.0%) than men (13.0%) and among younger adults. American Indian and Alaska Native non-Hispanic adults were the most likely to experience frequent fatigue (25.5%) among all race and Hispanic-origin groups, while Asian non-Hispanic adults were the least likely (9.1%). The prevalence of frequent fatigue decreased with increasing family income, was higher in the South and Midwest, and increased with decreasing urbanization level. Duration and intensity of fatigue symptoms varied within the population reporting frequent fatigue. Adults with frequent fatigue were more likely to report co-occurring functioning difficulties than other adults. About one-half of adults with frequent fatigue reported difficulties in at least three functioning domains, compared with about 16.9% of adults without frequent fatigue. Among adults with frequent fatigue, 29.0% reported limitations participating in social activities and 36.0% reported work limitations.

## Introduction

Fatigue is generally defined as physical or mental tiredness or exhaustion that does not improve with additional sleep or rest (1–3). It should be distinguished from sleepiness, which is the experience of feeling drowsy or having difficulty staying awake (4,5). Fatigue is one of the most frequently reported health concerns in primary care (6,7). While fatigue symptoms can be associated with various conditions (8–10), some fatigue symptoms may not be linked to a specific medical condition (11). In addition, fatigue is associated with both poorer health outcomes and a heightened risk of mortality in the general population (7). Despite the association with health and well-being, the frequency of fatigue symptoms in the general U.S. population is an underexplored topic (12).

Fatigue is considered an aspect of functioning (13). People who experience fatigue often also report difficulties in other domains of functioning (14), such as difficulty concentrating (15,16), mobility limitations (17,18), and psychosocial problems (19,20). Because fatigue symptoms often co-occur with difficulty functioning in other domains, the impact of fatigue on daily life can be compounded by the impact of these other functioning difficulties. This complex relationship between fatigue and functioning has important implications for everyday life. Overall, people who report fatigue symptoms are at higher risk of activity limitations (21,22) and disability, including permanent work disability (4,23,24).

This report presents nationally representative estimates on the frequency of fatigue symptoms in the adult population. The report’s focus is on fatigue symptoms themselves and not the underlying causes of fatigue or fatigue associated with specific medical conditions. The report also describes sociodemographic and geographic differences in the prevalence of frequent fatigue, defined as experiencing fatigue every day or most days during the past 3 months. The duration and intensity of fatigue symptoms among those reporting frequent fatigue are also included. Finally, the report describes the co-occurrence of frequent fatigue and other functioning difficulties, as well as the association between frequent fatigue and limitations participating in work and social activities.

## Methods

### Data source

Data from the 2024 National Health Interview Survey (NHIS) were used for this analysis. NHIS is a nationally representative household survey of the U.S. civilian noninstitutionalized population. It is conducted continuously throughout the year by the National Center for Health Statistics (NCHS). Interviews are typically initiated face-to-face in respondents’ homes with follow-ups conducted over the telephone as needed. The response rate to the Sample Adult interview in 2024 was 47.9% (25). NHIS does not include people in long-term care institutions (for example, nursing homes or hospitals for the chronically ill or for people with physical or intellectual disabilities); consequently, the estimates presented here represent the community-dwelling population only. For more information about the survey, visit the NHIS website (https://www.cdc.gov/nchs/nhis/index.htm).

### Measures

#### Fatigue

The NHIS measure of fatigue symptoms is based on responses to a set of three questions included in NHIS every other year about the frequency, intensity, and duration of feeling “very tired or exhausted” in the past 3 months. Frequency of fatigue symptoms was based on responses to the question, “In the past 3 months, how often did you feel very tired or exhausted? Would you say never, some days, most days, or every day?” Those who responded “most days” or “every day” to this initial question about fatigue symptoms were identified as experiencing frequent fatigue.

Follow-up questions about duration and intensity were asked for those reporting feeling very tired or exhausted at least some days to the initial question. Fatigue duration is measured based on responses to the question, “Thinking about the last time you felt very tired or exhausted, how long did it last?” Response options were “some of the day,” “most of the day,” or “all of the day.” Fatigue intensity is measured based on responses to the second follow-up question, “Thinking about the last time you felt this way, how would you describe the level of tiredness? Would you say a little, a lot, or somewhere in between?” In this report, fatigue duration and intensity are reported for adults experiencing frequent fatigue.

#### Sociodemographic and geographic characteristics

Fatigue symptoms are reported for selected sociodemographic and geographic characteristics for adults age 18 and older and include: age group, sex, race and Hispanic origin, family income as a percentage of the federal poverty level (FPL), region, and urbanization level. See Technical Notes for additional information.

#### Functioning difficulties

Measures of functioning difficulties include indicators for the domains of functioning in the Washington Group Short Set on Functioning—Enhanced (WG-SS Enhanced). The WG-SS Enhanced was developed to produce internationally comparable data on functioning in adults, including overall functioning, functioning in individual domains, and level or severity of functioning difficulties. It was finalized and adopted for use by the Washington Group on Disability Statistics (WG) (26,27). The questions use the International Classification of Functioning, Disability, and Health (ICF) as a conceptual framework (28). The WG-SS Enhanced adopts a functional approach to operationalization, assessing difficulty across basic, universal activity domains: seeing, hearing, walking, communication, cognition, self-care, upper body, and affect (anxiety and depression).

For this analysis, indicators of difficulties in functioning were created for each individual functional domain. For most WG-SS Enhanced domains, only one question is used to assess difficulty. For these domains (seeing, hearing, walking, communication, cognition, and self-care), a dichotomous indicator of “no difficulty” or “some difficulty or more” was created based on the response to each question. As a category, “some difficulty or more” combined responses of “some difficulty,” “a lot of difficulty,” and “cannot do at all.” For the upper body domain, two questions were asked to collect difficulty functioning, and the dichotomous indicator was created based on the highest level of difficulty reported across the two questions. For the anxiety and depression domains, which ask about frequency of symptoms, responses of “never” and “a few times a year” were categorized as “no difficulty” on the dichotomous indicator, while responses of “monthly,” “weekly,” and “daily” were categorized as “some difficulty or more.” See Technical Notes for additional information.

#### Participation limitations

Measures of work and social activities were included to describe associations between fatigue and limitations in participation. The measure of work limitations is based on responses to the question, “Are you limited in the kind or amount of work you can do because of a physical, mental, or emotional problem?” The response options were “yes” or “no.”

The measure of social activity limitations is based on responses to the question, “Because of a physical, mental, or emotional condition, do you have difficulty participating in social activities, such as visiting friends, attending clubs and meetings, or going to parties?” The four response options include: “no difficulty,” “some difficulty,” “a lot of difficulty,” and “cannot do at all.”

### Statistical analysis

The analytic sample was restricted to adults age 18 and older with a valid response to the question about frequency of experiencing fatigue in the past 3 months (n = 31,917). Respondents missing this information (2.0% of cases) were excluded. Percentages and the corresponding variances were calculated using R version 4.4.0. Point estimates and standard errors were calculated using the surveytable (https://cdcgov.github.io/surveytable/) package in R to account for the complex sample design of NHIS. All estimates were based on self-report and meet NCHS presentation standards for proportions (29). Differences between percentages were evaluated using two-sided significance tests at the 0.05 level. Linear and quadratic trends by age group, family income, and urbanization level were evaluated using orthogonal polynomials in logistic regression. “More likely” indicates a statistically significant difference. Lack of comment regarding the difference between any two estimates does not necessarily mean that the difference was tested and not found to be significant.

## Results

### Frequency of fatigue symptoms

In 2024, 28.5% of adults reported no symptoms of fatigue—that is, they never felt very tired or exhausted—in the past 3 months (Figure 1, Table 1). Just over one-half of adults (54.9%) reported feeling very tired or exhausted some days in the past 3 months, with an additional 10.7% reporting feeling very tired or exhausted most days and 5.9% every day.

Figure 1 Percent distribution of how often adults age 18 and older experienced fatigue in the past 3 months: United States, 2024

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

Figure 1 is a bar chart showing the percent distribution of how often adults age 18 and older experienced fatigue in the past 3 months in the United States in 2024.

Table 1

Percent distribution of how often adults age 18 and older experienced fatigue in the past 3 months: United States, 2024

Response | Percent (95% confidence interval)
Never | 28.5 (27.8–29.2)
Some days | 54.9 (54.2–55.6)
Most days | 10.7 (10.3–11.2)
Every day | 5.9 (5.5–6.3)

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

### Frequent fatigue

The percentage of adults who experienced frequent fatigue (defined as reporting fatigue every day or most days) was 16.6%. Women (20.0%) were more likely than men (13.0%) to experience frequent fatigue (Figure 2, Table 2). Frequent fatigue was highest among American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native) adults (25.5%), followed by White non-Hispanic (subsequently, White) adults (18.0%), Black non-Hispanic (subsequently, Black) adults (17.3%), and adults of Hispanic origin (12.9%), with Asian non-Hispanic (subsequently, Asian) adults (9.1%) being the least likely to experience frequent fatigue.

Figure 2 Percentage of adults age 18 and older who experienced frequent fatigue, by sex and race and Hispanic origin: United States, 2024

* Significantly different from men (p < 0.05).

† Significantly different from White adults (p < 0.05).

§ Significantly different from Black adults (p < 0.05).

¶ Significantly different from Hispanic adults (p < 0.5).

** Significantly different from Asian adults (p < 0.05).

NOTES: Categories shown for non-Hispanic adults are for those who selected only one racial group. Hispanic adults may be of any race or combination of races. Estimates for non-Hispanic adults of other or multiple races are not shown, but they are included in total estimates. Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

Figure 2 is a bar chart showing the percentage of adults age 18 and older who experienced frequent fatigue by sex and race and Hispanic origin in the United States in 2024.

Table 2

Percentage of adults age 18 and older who experienced fatigue in the past 3 months, by selected characteristics and frequency of fatigue: United States, 2024

Characteristic | Frequency
Characteristic | Never | Some days | Most days or every day(frequent fatigue)
| Percent (95% confidence interval)
Total | 28.5 (27.8–29.2) | 54.9 (54.2–55.6) | 16.6 (16.1–17.2)
Sex
Men | 33.1^*^ (32.1–34.2) | 53.8^*^ (52.7–54.9) | 13.0^*^ (12.4–13.7)
Women | 24.1 (23.2–25.0) | 56.0 (55.0–57.0) | 20.0 (19.2–20.8)
Age group (years)
18–34 | 25.4^†^ (24.0–26.8) | 55.2^†^ (53.7–56.6) | 19.5^§^ (18.4–20.7)
35–49 | 24.7 (23.4–26.0) | 57.9 (56.6–59.3) | 17.4 (16.3–18.4)
50–64 | 30.2 (28.9–31.6) | 53.8 (52.4–55.2) | 16.0 (14.9–17.1)
65 and older | 34.5 (33.4–35.7) | 52.6 (51.5–53.7) | 12.9 (12.1–13.7)
Race and Hispanic origin
American Indian and Alaska Native, non-Hispanic | 28.3^¶,**^ (21.0–36.6) | 46.2^††^ (37.5–55.0) | 25.5^¶,**,††,§§^ (18.5–33.6)
White, non-Hispanic | 25.4^¶,**,§§^ (24.6–26.2) | 56.6^¶,§§^ (55.7–57.5) | 18.0^¶,**^ (17.3–18.6^)^
Black, non-Hispanic | 29.3^¶,**^ (27.2–31.3) | 53.4 (51.3–55.5) | 17.3^¶,**^ (15.7–19.1)
Hispanic | 36.2 (34.4–38.0) | 50.9 (49.1–52.7) | 12.9^**^ (11.8–14.1)
Asian, non-Hispanic | 37.4 (34.5–40.3) | 53.5 (50.5–56.6) | 9.1 (7.4–11.0)
Family income
Less than 100% FPL | 29.1^†^ (26.8–31.5) | 49.2^§^ (46.7–51.7) | 21.7^§^ (19.8–23.7)
100% to less than 200% | 27.4 (25.8–29.1) | 52.6 (50.8–54.4) | 19.9 (18.6–21.3)
200% to less than 400% | 27.0 (25.8–28.2) | 55.8 (54.4–57.1) | 17.3 (16.3–18.3)
400% FPL or more | 29.8 (28.8–30.8) | 56.6 (55.5–57.6) | 13.6 (12.9–14.4)
Region
South | 29.3^¶¶^ (28.0–30.6) | 53.0^¶¶,***,†††^ (51.7–54.2) | 17.7^***,†††^ (16.7–18.8)
Midwest | 25.2^***,†††^ (23.8–26.5) | 57.4^***^ (55.8–59.0) | 17.5^***,†††^ (16.4–18.6)
West | 29.3 (27.9–30.7) | 55.2 (53.8–56.6) | 15.6 (14.6–16.6)
Northeast | 29.5 (27.9–31.1) | 56.0 (54.3–57.6) | 14.5 (13.3–15.8)
Urbanization level
Large central metropolitan | 30.6^§^ (29.4–31.9) | 54.9 (53.6–56.2) | 14.5^§^ (13.6–15.4)
Large fringe metropolitan | 29.3 (27.9–30.7) | 55.1 (53.5–56.7) | 15.6 (14.5–16.8)
Medium and small metropolitan | 27.2 (25.8–28.5) | 54.9 (53.6–56.2) | 17.9 (16.9–18.9)
Nonmetropolitan | 25.0 (23.3–26.6) | 54.6 (52.9–56.2) | 20.5 (19.1–21.9)

* Significantly different from women (p < 0.05).

† Significant quadratic trend (p < 0.05).

§ Significant linear trend (p < 0.05).

¶ Significantly different from Hispanic adults (p < 0.05).

** Significantly different from Asian adults (p < 0.05).

†† Significantly different from White adults (p < 0.05).

§§ Significantly different from Black adults (p < 0.05).

¶¶ Significantly different from adults in the Midwest (p < 0.05).

*** Significantly different from adults in the West (p < 0.05).

††† Significantly different from adults in the Northeast (p < 0.05).

NOTES: Categories shown for non-Hispanic adults are for those who selected only one racial group. Hispanic adults may be of any race or combination of races. Estimates for non-Hispanic adults of other or multiple races are not shown, but they are included in total estimates. FPL is federal poverty level. Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

The percentage of adults who experienced frequent fatigue decreased with increasing age, from 19.5% among those ages 18–34, 17.4% among those ages 35–49, and 16.0% among those ages 50–64 to 12.9% among those age 65 and older (Table 2). The percentage of adults reporting frequent fatigue decreased with increasing family income, with the highest prevalence of frequent fatigue among adults with family incomes less than 100% of FPL (21.7%) and the lowest prevalence among adults with family incomes at or above 400% FPL (13.6%).

Adults living in the South (17.7%) and Midwest (17.5%) were more likely to experience frequent fatigue than adults living in the West (15.6%) or Northeast (14.5%). The prevalence of frequent fatigue increased with decreasing urbanization level, from 14.5% in large central metropolitan areas, 15.6% in large fringe metropolitan areas, and 17.9% in medium and small metropolitan areas to 20.5% in nonmetropolitan areas.

### Duration and intensity of fatigue

The duration and intensity of fatigue symptoms experienced by adults reporting frequent fatigue is presented in Figure 3 and Table 3. Most adults with frequent fatigue said their fatigue symptoms typically lasted some of the day (45.3%) or most of the day (34.5%), though about one in five reported that their fatigue symptoms lasted all day long (20.2%). Among adults with frequent fatigue, 14.5% described their level of fatigue as a little, 38.8% as a lot, and 46.8% as somewhere between a little and a lot.

Figure 3 Percent distribution of fatigue duration and intensity among adults age 18 and older who experienced frequent fatigue: United States, 2024

NOTES: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population. Estimates may not add to 100 due to rounding.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

Figure 3 is a bar chart showing the percent distribution of fatigue duration and intensity among adults age 18 and older who experienced frequent fatigue in the United States in 2024.

Table 3

Percent distribution of fatigue duration and intensity among adults age 18 and older who experienced frequent fatigue: United States, 2024

Duration and intensity of fatigue symptoms | Experienced frequent fatigue
Duration and intensity of fatigue symptoms | Percent(95% confidence interval) | Standard error
Duration
Some of the day | 45.3 (43.6–47.0) | 0.9
Most of the day | 34.5 (33.0–36.1) | 0.8
All day | 20.2 (18.9–21.6) | 0.7
Intensity
A little | 14.5 (13.2–15.7) | 0.6
Somewhere between a little and a lot | 46.8 (45.1–48.4) | 0.8
A lot | 38.8 (37.2–40.4) | 0.8

NOTES: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population. Estimates may not add to 100 due to rounding.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

### Co-occurrence of functioning difficulties

Across all nine domains of functioning described, adults who experienced frequent fatigue were more likely to report functioning difficulties than adults who did not experience frequent fatigue (Table 4). The three most frequently co-occurring functioning difficulties reported by adults who experienced frequent fatigue were symptoms of anxiety (69.6%), cognition difficulty (46.1%), and symptoms of depression (45.0%). Compared with adults without frequent fatigue, adults who experienced frequent fatigue were more than three times as likely to have symptoms of depression and about twice as likely to report cognition difficulty or symptoms of anxiety. The least frequently reported co-occurring functioning difficulty among adults with frequent fatigue was difficulty communicating (11.1%), which was reported by 4.7% of adults without frequent fatigue.

Table 4

Percent distribution of adults age 18 and older who reported selected functioning difficulties, by experience of frequent fatigue and number of domains: United States, 2024

Domain of functioning | With frequent fatigue | Without frequent fatigue
Seeing | Percent (95% confidence interval)
No difficulty | 70.2^*^ (68.6–71.7) | 84.4 (83.8–85.0)
Some difficulty or more | 29.8^*^ (28.3–31.4) | 15.6 (15.0–16.2)
Hearing
No difficulty | 76.1^*^ (74.8–77.5) | 85.9 (85.4–86.5)
Some difficulty or more | 23.9^*^ (22.5–25.2) | 14.1 (13.5–14.6)
Walking
No difficulty | 66.5^*^ (64.9–68.1) | 84.8 (84.3–85.4)
Some difficulty or more | 33.5^*^ (31.9–35.1) | 15.2 (14.6–15.7)
Communication
No difficulty | 88.9^*^ (87.7–90.0) | 95.3 (94.9–95.6)
Some difficulty or more | 11.1^*^ (10.0–12.3) | 4.7 (4.4–5.1)
Cognition
No difficulty | 53.9^*^ (52.2–55.7) | 80.8 (80.2–81.5)
Some difficulty or more | 46.1^*^ (44.3–47.8) | 19.2 (18.5–19.8)
Self care
No difficulty | 87.8^*^ (86.6–88.9) | 96.9 (96.6–97.2)
Some difficulty or more | 12.2^*^ (11.1–13.4) | 3.1 (2.8–3.4)
Upper body
No difficulty | 79.3^*^ (77.9–80.6) | 92.3 (91.9–92.7)
Some difficulty or more | 20.7^*^ (19.4–22.1) | 7.7 (7.3–8.1)
Anxiety
No difficulty | 30.4^*^ (28.8–32.0) | 65.0 (64.1–65.8)
Some difficulty or more | 69.6^*^ (68.0–71.2) | 35.0 (34.2–35.9)
Depression
No difficulty | 55.0^*^ (53.4–56.7) | 87.3 (86.8–87.8)
Some difficulty or more | 45.0^*^ (43.3–46.6) | 12.7 (12.2–13.2)
Number of domains with functioning difficulties
None | 10.9^*^ (9.9–12.0) | 39.1 (38.3–40.0)
One | 17.3^*^ (16.0–18.6) | 27.4 (26.8–28.1)
Two | 20.9^*^ (19.5–22.4) | 16.5 (16.0–17.1)
Three or more | 50.9^*^ (49.1–52.6) | 16.9 (16.3–17.6)

* Significantly different from adults without frequent fatigue (p < 0.05).

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

Most adults reported difficulties in at least one of the nine domains of functioning, regardless of fatigue symptom frequency (Figure 4, Table 4). About one in five adults with frequent fatigue reported co-occurring functioning difficulties in two domains (20.9%) compared with 16.5% of adults without frequent fatigue. Moreover, about one-half of adults with frequent fatigue reported functioning difficulties in three or more domains (50.9%) compared with 16.9% of adults without frequent fatigue.

Figure 4 Percent distribution of adults age 18 and older with functioning difficulties, by experience of frequent fatigue and number of domains: United States, 2024

* Significantly different from adults without frequent fatigue (p < 0.05).

NOTES: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population. Estimates may not add to 100 due to rounding.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

Figure 4 is a stacked bar chart showing the percent distribution of adults age 18 and older with functioning difficulties by experience of frequent fatigue and number of domains in the United States in 2024.

### Participation limitations

Adults who experienced frequent fatigue were more likely than adults without frequent fatigue to report limitations in participation (Figure 5, Table 5). Just over one-third of adults who experienced frequent fatigue reported limitations in the kind or amount of work they can do (36.0%), compared with 15.3% of adults without frequent fatigue. Limitations in social activities were also more common among the population with frequent fatigue: Among adults with frequent fatigue, 16.2% reported some difficulty participating in social activities, such as visiting friends, attending clubs and meetings, or going to parties, compared with 5.3% of adults without frequent fatigue. Similarly, 8.5% of adults with frequent fatigue reported a lot of difficulty participating in social activities, and 4.3% reported social activities were something they cannot do at all, compared with 1.5% and 1.1% of adults without frequent fatigue, respectively.

Figure 5 Percentage of adults age 18 and older who reported participation limitations, by experience of frequent fatigue: United States, 2024

* Significantly different from adults without frequent fatigue (p < 0.05).

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

Figure 5 is a bar chart showing the percentage of adults age 18 and older who reported participation limitations by experience of frequent fatigue in the United States in 2024.

Table 5

Percentage of adults age 18 and older who reported participation limitations, by experience of frequent fatigue: United States, 2024

Participation limitation type | With frequent fatigue | Without frequent fatigue
Work | Percent (95% confidence interval)
No | 64.0^*^ (62.2–65.7) | 84.7 (84.1–85.3)
Yes | 36.0^*^ (34.3–37.8) | 15.3 (14.7–15.9)
Social activity
No difficulty | 71.0^*^ (69.4–72.6) | 92.0 (91.6–92.5)
Some difficulty | 16.2^*^ (14.9–17.6) | 5.3 (4.9–5.7)
A lot of difficulty | 8.5^*^ (7.6–9.5) | 1.5 (1.4–1.7)
Cannot do at all | 4.3^*^ (3.6–5.0) | 1.1 (1.0–1.3)

* Significantly different from adults without frequent fatigue (p < 0.05).

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

## Discussion

This report uses NHIS data to describe the prevalence of fatigue symptoms among adults in the United States by sociodemographic and geographic characteristics, as well as to describe co-occurring functioning difficulties and work and social activity limitations among adults with frequent fatigue. In 2024, nearly three-quarters of adults reported symptoms of fatigue at least some days in the past 3 months, with 16.6% of adults experiencing frequent fatigue (defined as having fatigue symptoms most days or every day). Frequent fatigue was more common among women than men and at younger ages, with the highest percentage among adults ages 18–34 and the lowest percentage among adults age 65 and older. American Indian and Alaska Native adults were more likely to experience frequent fatigue than adults of any other race and Hispanic-origin group, while Asian adults were the least likely to report frequent fatigue. Frequent fatigue decreased with increasing family income and urbanization level, and was more common in the South and Midwest than in other regions. Among adults who frequently experienced fatigue symptoms, about one-half reported that the last time they experienced frequent fatigue, the duration lasted most or all of the day, and more than one-third described the level of fatigue (intensity) as a lot.

Frequent symptoms of fatigue may indicate underlying health problems and may co-occur with difficulty functioning in other domains. Overall, 89.1% of adults who experienced frequent fatigue reported co-occurring functioning difficulties in at least one of the nine other domains, with about one-half (50.9%) reporting difficulties in three or more domains of functioning. In contrast, 60.8% of adults without frequent fatigue reported functioning difficulties in at least one domain and 16.9% reported difficulties in three or more domains. The prevalences of cognition difficulty and symptoms of depression and anxiety were particularly high among adults with frequent fatigue compared with other domains.

Frequent fatigue symptoms may interfere with everyday activities in work and personal life. Adults who reported frequent fatigue were more likely to report participation limitations in work and social activities than adults without frequent fatigue. For example, more than one in three adults with frequent fatigue reported being limited in the kind or amount of work they can do because of a physical, mental, or emotional problem, compared with fewer than one in six adults without frequent fatigue.

As with all studies using cross-sectional data such as NHIS, it is not possible to determine causation when exploring the association between fatigue symptoms and other characteristics. The association between frequent fatigue and functioning difficulties, for example, may result from fatigue symptoms affecting functioning, or be due to an underlying condition producing both fatigue symptoms and difficulty functioning (such as poststroke patients, who might experience both fatigue and cognition difficulties), or be the consequence of a combination of these and other factors.

Previous studies of fatigue have generally focused on subpopulations with specific medical conditions, such as cancer patients (30) or adults with multiple sclerosis (31). An earlier NCHS publication described the prevalence of myalgic encephalomyletis (ME), or chronic fatigue syndrome (CFS), in the United States (32). This report’s approach differs by measuring general fatigue symptoms among all adults, an approach that avoids excluding adults whose fatigue symptoms may be unexplained or whose underlying condition is undiagnosed. As such, this report provides a unique look at the prevalence and distribution of fatigue symptoms that are not condition-specific in the general U.S. population, as well as a profile of functioning in the population experiencing frequent fatigue. The observed higher rates of participation limitations in work and social activities among adults with frequent fatigue may inform additional research on the implications of frequent fatigue symptoms for social and economic life, regardless of the underlying cause or causes of fatigue.

## Acknowledgments

The authors acknowledge Kathi Huddleston, Alan Simon, and Cathy Burt for their comments on earlier drafts of this report, and Stephen Pitts for providing definitions of the types of ED physicians and other technical assistance.

## Technical Notes

### Definitions

#### Selected sociodemographic and geographic measures

Family income as a percentage of federal poverty level (FPL)Estimates are based on FPL, which is calculated from family income and family size using the U.S. Census Bureau’s poverty thresholds for the previous calendar year (33). Family income was defined as less than 100% FPL, 100% to less than 200% FPL, 200% to less than 400% FPL, and 400% FPL or more. Family income was calculated using National Health Interview Survey imputed income files (34).

Race and Hispanic origin—Respondents were grouped into five categories: Hispanic adults of any race, White non-Hispanic adults, Black or African American non-Hispanic adults, Asian non-Hispanic adults, and American Indian and Alaska Native non-Hispanic adults. These categories were based on responses to two questions asking about race and Hispanic origin, where those characterized as Hispanic may be of any race or combination of races. People who reported more than one race or multiple races were not reported but were included in the overall analysis.

Region—Corresponds to the regions recognized by the U.S. Census Bureau and are defined as Northeast (Connecticut, Maine, Massachusetts, New Hampshire, New Jersey, New York, Pennsylvania, Rhode Island, and Vermont); Midwest (Illinois, Indiana, Iowa, Kansas, Michigan, Minnesota, Missouri, Nebraska, North Dakota, Ohio, South Dakota, and Wisconsin); South (Alabama, Arkansas, Delaware, District of Columbia, Florida, Georgia, Kentucky, Louisiana, Maryland, Mississippi, North Carolina, Oklahoma, South Carolina, Tennessee, Texas, Virginia, and West Virginia); and West (Alaska, Arizona, California, Colorado, Hawaii, Idaho, Montana, Nevada, New Mexico, Oregon, Utah, Washington, and Wyoming).

Urbanization level—Based on the National Center for Health Statistics (NCHS) Urban–Rural Classification Scheme for Counties (35). The NCHS urban–rural classification is based on metropolitan statistical area status, defined by the Office of Management and Budget according to published standards that are applied to U.S. Census Bureau data. This report includes the four-level condensed NCHS urban–rural classification available in the public-use data set: large central metropolitan (similar to inner cities), large fringe metropolitan (similar to suburbs), medium and small metropolitan, and nonmetropolitan. Large metropolitan areas have populations of 1 million or more. Metropolitan areas with populations less than 1 million are classified as medium (populations of 250,000–999,999) or small (populations less than 250,000).

#### Functioning measures for individual functional domains

Seeing—Based on a response to the question, “Do you have difficulty seeing even when wearing glasses or contact lenses?” Response options are: “no difficulty,” “some difficulty,” “a lot of difficulty,” or “cannot do at all.” Two categories were created based on reported level of difficulty: no difficulty and some difficulty or more (includes responses of “some difficulty,” “a lot of difficulty,” and “cannot do at all”).

Hearing—Based on a response to the question, “Do you have difficulty hearing even when using your hearing aid?” Response options are: “no difficulty,” “some difficulty,” “a lot of difficulty,” or “cannot do at all.” Two categories were created based on reported level of difficulty: no difficulty and some difficulty or more (includes responses of “some difficulty,” “a lot of difficulty,” and “cannot do at all”).

Walking—Based on a response to the question, “Do you have difficulty walking or climbing steps?” Response options are: “no difficulty,” “some difficulty,” “a lot of difficulty,” or “cannot do at all.” Two categories were created based on reported level of difficulty: no difficulty and some difficulty or more (includes responses of “some difficulty,” “a lot of difficulty,” and “cannot do at all”).

Communication—Based on a response to the question, “Using your usual language, do you have difficulty communicating, for example, understanding or being understood?” Response options are: “no difficulty,” “some difficulty,” “a lot of difficulty,” or “cannot do at all.” Two categories were created based on reported level of difficulty: no difficulty and some difficulty or more (includes responses of “some difficulty,” “a lot of difficulty,” and “cannot do at all”).

Cognition—Based on a response to the question, “Do you have difficulty remembering or concentrating?” Response options are: “no difficulty,” “some difficulty,” “a lot of difficulty,” or “cannot do at all.” Two categories were created based on reported level of difficulty: no difficulty and some difficulty or more (includes responses of “some difficulty,” “a lot of difficulty,” and “cannot do at all”).

Self-care—Based on a response to the question, “Do you have difficulty with self-care, such as washing all over or dressing?” Response options are: “no difficulty,” “some difficulty,” “a lot of difficulty,” or “cannot do at all.” Two categories were created based on reported level of difficulty: no difficulty and some difficulty or more (includes responses of “some difficulty,” “a lot of difficulty,” and “cannot do at all”).

Upper body—Based on responses to two questions, “Do you have difficulty raising a 2-liter bottle of water or soda from waist to eye level?” and “Do you have difficulty using your hands and fingers, such as picking up small objects, for example, a button or pencil, or opening or closing containers or bottles?” Response options are: “no difficulty,” “some difficulty,” “a lot of difficulty,” or “cannot do at all.” Two categories were created based on the highest level of difficulty reported across the two questions: no difficulty and some difficulty or more (includes responses of “some difficulty,” “a lot of difficulty,” and “cannot do at all”).

Anxiety—Based on a response to the question, “How often do you feel worried, nervous or anxious?” Response options are: “never,” “a few times a year,” “monthly,” “weekly,” and “daily.” Two categories were created: no difficulty (responses of “never” and “a few times a year”), and some difficulty or more (includes responses of “monthly,” “weekly,” and “daily”).

Depression—Based on a response to the question, “How often do you feel depressed?” Response options are: “never,” “a few times a year,” “monthly,” “weekly,” and “daily.” Two categories were created: no difficulty (responses of “never” and “a few times a year”), and some difficulty or more (includes responses of “monthly,” “weekly,” and “daily”).

## References

1 Cella D, Peterman A, Passik S, Jacobsen P, Breitbart W. Progress toward guidelines for the management of fatigue. Oncology (Williston Park). 1998 Nov;12(11A):369–77.10028520
2 Knoop V, Cloots B, Costenoble A, Debain A, R Vella Azzopardi S, Vermeiren, et al. Fatigue and the prediction of negative health outcomes: A systematic review with meta-analysis. Ageing Res Rev. 2021 May;67:101261.33548508
3 Poluri A, Mores J, Cook DB, Findley TW, Cristian A. Fatigue in the elderly population. Phys Med Rehabil Clin N Am. 2005 Feb;16(1):91–108.15561546
4 Shen J, Barbera J, Shapiro CM. Distinguishing sleepiness and fatigue: Focus on definition and measurement. Sleep Med Rev. 2006 Feb;10(1):63–76.16376590
5 Suh S, Lok R, Weed L, Cho A, Mignot E, Leary EB, et al. Fatigued but not sleepy? An empirical investigation of the differentiation between fatigue and sleepiness in sleep disorder patients in a cross-sectional study. J Psychosom Res. 2024 Mar;178:111606.38359639
6 Finley CR, Chan DS, Garrison S, Korownyk C, Kolber MR, Campbell S, et al. What are the most common conditions in primary care? Systematic review. Can Fam Physician. 2018 Nov;64(11):832–40.30429181
7 Yoon JH, Park NH, Kang YE, Ahn YC, Lee EJ, Son CG. The demographic features of fatigue in the general population worldwide: A systematic review and meta-analysis. Front Public Health. 2023 Jul;11:1192121.37575103
8 Deary V, Hagenaars SP, Harris SE, Hill WD, Davies G, Liewald DCM, et al. Genetic contributions to self-reported tiredness. Mol Psychiatry. 2018 Mar;23(3):609–20.
9 Elnicki DM, Shockcor WT, Brick JE, Beynon D. Evaluating the complaint of fatigue in primary care: Diagnoses and outcomes. Am J Med. 1992 Sep;93(3):303–6.1524082
10 Goërtz YMJ, Braamse AMJ, Spruit MA, Janssen DJA, Ebadi Z, Van Herck M, et al. Fatigue in patients with chronic disease: Results from the population-based Lifelines Cohort Study. Sci Rep. 2021 Oct;11(1):20977.
11 Torres-Harding S, Jason LA. What is fatigue? History and epidemiology. In: DeLuca J, editor. Fatigue as a window to the brain. Cambridge, MA: The MIT Press; 2005. p. 3–17.
12 Lewis G, Wessely S. The epidemiology of fatigue: More questions than answers. J Epidemiol Community Health. 1992 Apr;46(2):92–7.1583440
13 Alghwiri AA, Almhdawi KA, Marchetti G. Are fatigue scales the same? A content comparison using the International Classification of Functioning, Disability and Health. Mult Scler Relat Disord. 2020 Nov;46:102596.33296990
14 Maetzler W, L Correia Guedes KN, Emmert J, Kudelka HL, Hildesheim E, Paulides, et al. Fatigue-related changes of daily function: Most promising measures for the digital age. Digit Biomark. 2024 Mar;8(1):30–9.38510264
15 Cockshell SJ, Mathias JL. Cognitive functioning in chronic fatigue syndrome: A meta-analysis. Psychol Med. 2010 Aug;40(8):1253–67.20047703
16 Humphrey L, Arbuckle R, Mease P, Williams DA, Samsoe BD, Gilbert C. Fatigue in fibromyalgia: A conceptual model informed by patient interviews. BMC Musculoskelet Disord. 2010 Sep;11:216.20854680
17 Garg H, Bush S, Gappmaier E. Associations between fatigue and disability, functional mobility, depression, and quality of life in people with multiple sclerosis. Int J MS Care. 2016 Mar-Apr;18(2):71–7.27134580
18 Schreurs KMG, de Ridder DTD, Bensing JM. Fatigue in multiple sclerosis: Reciprocal relationships with physical disabilities and depression. J Psychosom Res. 2002 Sep;53(3):775–81.12217451
19 Brown LF, Kroenke K. Cancer-related fatigue and its associations with depression and anxiety: A systematic review. Psychosomatics. 2009 Sep-Oct;50(5):440–7.19855028
20 Corfield EC, Martin NG, Nyholt DR. Co-occurrence and symptomatology of fatigue and depression. Compr Psychiatry. 2016 Nov;71:1–10.27567301
21 Salter A, Fox RJ, Tyry T, Cutter G, Marrie RA. The association of fatigue and social participation in multiple sclerosis as assessed using two different instruments. Mult Scler Relat Disord. 2019 Jun;31:165–72.31063935
22 Yu DSF, Lee DTF, Man NW. Fatigue among older people: A review of the research literature. Int J Nurs Stud. 2010 Feb;47(2):216–28.19524240
23 van Amelsvoort LGPM, Kant IJ, Beurskens AJHM, Schröer CAP, Swaen GMH. Fatigue as a predictor of work disability. Occup Environ Med. 2002 Oct;59(10):712–3.12356934
24 Vestergaard S, Nayfield SG, Patel KV, Eldadah B, Cesari M, Ferrucci L, et al. Fatigue in a representative population of older persons and its association with functional impairment, functional limitation, and disability. J Gerontol A Biol Sci Med Sci. 2009 Jan;64(1):76–82.19176328
25 National Center for Health Statistics. National Health Interview Survey: 2024 survey description. National Center for Health Statistics; 2025 Jul. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/NHIS/2024/srvydesc-508.pdf.
26 Weeks JD. Background and origin of the Washington Group: Improving the state of disability data. In: Altman BM, editor. International measurement of disability: Purpose, method and application. Springer International Publishing; 2016. p. 3–14.
27 Washington Group on Disability Statistics. The Washington Group Short Set on Functioning—Enhanced (WG–SS Enhanced). 2022. Available from: https://www.washingtongroup-disability.com/question-sets/wg-short-set-on-functioning-enhanced-wg-ss-enhanced/.
28 World Health Organization. International classification of functioning, disability, and health (ICF). Available from: https://www.who.int/standards/classifications/international-classification-of-functioning-disability-and-health.
29 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. Vital Health Stat 2. 2017 Aug;(175):1–22.
30 White B, Renzi C, Barclay M, Lyratzopoulos G. Underlying cancer risk among patients with fatigue and other vague symptoms: A population-based cohort study in primary care. Br J Gen Pract. 2023 Jan;73(727):e75–e87.36702593
31 Berger JR, Pocoski J, Preblick R, Boklage S. Fatigue heralding multiple sclerosis. Mult Scler. 2013 Oct;19(11):1526–32.23439577
32 Vahratian A, Js Lin, Bertolli J, Unger Er. Myalgic encephalomyelitis/chronic fatigue syndrome in adults: United States, 2021–2022. NCHS Data Brief. 2023 Dec;(488):1–8. DOI: 10.15620/cdc:134504.
33 U.S. Census Bureau. Poverty thresholds. 2023. Available from: https://www.census.gov/data/tables/time-series/demo/income-poverty/historical-poverty-thresholds.html.
34 National Center for Health Statistics. Multiple imputation of family income in 2023 National Health Interview Survey: Methods. 2024. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/NHIS/2023/NHIS2023-imputation-techdoc-508.pdf.
35 National Center for Health Statistics. NCHS urban–rural classification scheme for counties. Available from: https://www.cdc.gov/nchs/data-analysis-tools/urban-rural.html.

National Center for Health Statistics

Carolyn M. Greene, M.D., Acting Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Analysis and Epidemiology

Irma E. Arispe, Ph.D., Director

Kimberly A. Lochner, Sc.D., Associate Director for Science