# Health E-Stat 113 Maternal Mortality Rates in the United States, 2024

### Introduction

This report presents maternal mortality rates in the United States for 2024.

### Methods

Data are from the National Vital Statistics System mortality file. Maternal mortality rates are per 100,000 live births, based on data from the national Vital Statistics natality file.

### Key findings

The maternal mortality rate for 2024 was 17.9 deaths per 100,000 live births. The rates were not statistically different from 2023 overall, by age, or by race and Hispanic-origin groups. The maternal mortality rates for women 40 and older were greater than those for women in younger age groups. The maternal mortality rates for Black non-Hispanic women were greater than those for other race and Hispanic groups.

This report presents maternal mortality for 2024 based on data from the National Vital Statistics System (NVSS) (1). A maternal death is defined as “the death of a woman while pregnant or within 42 days of termination of pregnancy, irrespective of the duration and the site of the pregnancy, from any cause related to or aggravated by the pregnancy or its management, but not from accidental or incidental causes” (2). Maternal mortality rates—the number of maternal deaths per 100,000 live births—are shown in this report by age group and race and Hispanic origin.

In 2024, 649 women died of maternal causes in the United States, compared with 669 in 2023 (1) (Figure 1, Table). The maternal mortality rate for 2024, 17.9 deaths per 100,000 live births, was not significantly lower than the rate of 18.6 in 2023.

In 2024, the maternal mortality rate for Black non-Hispanic (subsequently, Black) women was 44.8 deaths per 100,000 live births, which was significantly higher than the rates for White non-Hispanic (subsequently, White) (14.2), Hispanic (12.1), and Asian non-Hispanic (subsequently, Asian) (18.1) women (Figure 2, Table). The observed decreases in 2024 for Black, White, and Hispanic women and the increase for Asian women were not significant.

Figure 1 Maternal mortality rate: United States, 2018–2024

^1^Statistically significant change in rate from previous year (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 1 is a line graph of the maternal mortality rate in the United States in 2018–2024.

Figure 2 Maternal mortality rate, by race and Hispanic origin: United States, 2023 and 2024

^1^Significantly different from Black non-Hispanic women (p < 0.05).

NOTES: Race groups are single race. People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 2 is a bar chart of the maternal mortality rate by race and Hispanic origin in the United States in 2023 and 2024.

Figure 3 Maternal mortality rate, by age group: United States, 2023 and 2024

^1^Significantly different from ages 25–39 and 40 and older (p < 0.05).

^2^Significantly different from age 40 and older (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 3 is a bar chart of the maternal mortality rate by age group in the United States in 2023 and 2024.

Table

Number of live births and maternal deaths, and maternal mortality rate, by race and Hispanic origin and age: United States, 2018–2024

Race and Hispanic origin and age | 2018 | 2019 | 2020 | 2021 | 2022 | 2023 | 2024
| Number of live births
Total^1^ | 3,791,712 | 3,747,540 | 3,613,647 | 3,664,292 | 3,667,758 | 3,596,017 | 3,628,934
Younger than 25 | 907,782 | 877,803 | 825,403 | 797,334 | 784,299 | 759,713 | 750,800
25–39 | 2,756,974 | 2,739,976 | 2,658,445 | 2,731,223 | 2,738,802 | 2,689,250 | 2,725,743
40 and older | 126,956 | 129,761 | 129,799 | 135,735 | 144,657 | 147,054 | 152,391
Asian, non-Hispanic^2^ | 240,798 | 238,769 | 219,068 | 213,813 | 218,994 | 215,738 | 226,860
Younger than 25 | 16,338 | 15,071 | 12,993 | 11,149 | 11,002 | 10,352 | 10,025
25–39 | 211,331 | 210,177 | 193,139 | 189,405 | 193,025 | 190,128 | 200,513
40 and older | 13,129 | 13,521 | 12,936 | 13,259 | 14,967 | 15,258 | 16,322
Black, non-Hispanic^2^ | 552,029 | 548,075 | 529,811 | 517,889 | 511,439 | 491,494 | 473,377
Younger than 25 | 176,243 | 169,853 | 159,541 | 149,435 | 140,498 | 131,977 | 123,063
25–39 | 358,276 | 360,206 | 351,648 | 349,170 | 349,740 | 337,697 | 327,982
40 and older | 17,510 | 18,016 | 18,622 | 19,284 | 21,201 | 21,820 | 22,332
White, non-Hispanic^2^ | 1,956,413 | 1,915,912 | 1,843,432 | 1,887,656 | 1,840,739 | 1,787,051 | 1,783,156
Younger than 25 | 391,829 | 374,129 | 348,666 | 336,792 | 324,604 | 309,033 | 301,335
25–39 | 1,504,888 | 1,480,595 | 1,433,839 | 1,486,249 | 1,449,365 | 1,410,849 | 1,412,086
40 and older | 59,696 | 61,188 | 60,927 | 64,615 | 66,770 | 67,169 | 69,735
Hispanic | 886,210 | 886,467 | 866,713 | 885,916 | 937,421 | 945,200 | 984,092
Younger than 25 | 275,553 | 270,948 | 258,635 | 255,806 | 264,310 | 266,416 | 274,850
25–39 | 579,553 | 584,109 | 576,690 | 597,703 | 637,735 | 642,429 | 672,341
40 and older | 31,104 | 31,410 | 31,388 | 32,407 | 35,376 | 36,355 | 36,901
| Number of maternal deaths
Total^1^ | 658 | 754 | 861 | 1,205 | 817 | 669 | 649
Younger than 25 | 96 | 111 | 114 | 163 | 113 | 95 | 103
25–39 | 458 | 544 | 607 | 854 | 578 | 486 | 451
40 and older | 104 | 98 | 140 | 188 | 126 | 88 | 95
Asian, non-Hispanic^2^ | 32 | 33 | 27 | 36 | 29 | 23 | 41
Younger than 25 | * | * | * | * | * | * | *
25–39 | 25 | 28 | 20 | 24 | 21 | 17 | 34
40 and older | * | * | * | * | * | * | *
Black, non-Hispanic^2^ | 206 | 241 | 293 | 362 | 253 | 247 | 212
Younger than 25 | 27 | 32 | 46 | 62 | 44 | 37 | 35
25–39 | 137 | 179 | 198 | 242 | 172 | 181 | 144
40 and older | 42 | 30 | 49 | 58 | 37 | 29 | 33
White, non-Hispanic^2^ | 291 | 343 | 352 | 503 | 350 | 259 | 254
Younger than 25 | 41 | 49 | 40 | 57 | 35 | 26 | 30
25–39 | 207 | 248 | 253 | 364 | 259 | 195 | 183
40 and older | 43 | 46 | 59 | 82 | 56 | 38 | 41
Hispanic | 105 | 112 | 158 | 248 | 158 | 117 | 119
Younger than 25 | 21 | 23 | 20 | 36 | 25 | 27 | 31
25–39 | 72 | 71 | 111 | 184 | 108 | 77 | 75
40 and older | 12 | 18 | 27 | 28 | 25 | 13 | 13
| Maternal mortality rate^3^
Total^1^ | 17.4 | 20.1 | 23.8 | 32.9 | 22.3 | 18.6 | 17.9
Younger than 25 | 10.6 | 12.6 | 13.8 | 20.4 | 14.4 | 12.5 | 13.7
25–39 | 16.6 | 19.9 | 22.8 | 31.3 | 21.1 | 18.1 | 16.5
40 and older | 81.9 | 75.5 | 107.9 | 138.5 | 87.1 | 59.8 | 62.3
Asian, non-Hispanic^2^ | 13.3 | 13.8 | 12.3 | 16.8 | 13.2 | 10.7 | 18.1
Younger than 25 | * | * | * | * | * | * | *
25–39 | 11.8 | 13.3 | 10.4 | 12.7 | 10.9 | 8.9 | 17.0
40 and older | * | * | * | * | * | * | *
Black, non-Hispanic^2^ | 37.3 | 44.0 | 55.3 | 69.9 | 49.5 | 50.3 | 44.8
Younger than 25 | 15.3 | 18.8 | 28.8 | 41.5 | 31.3 | 28.0 | 28.4
25–39 | 38.2 | 49.7 | 56.3 | 69.3 | 49.2 | 53.6 | 43.9
40 and older | 239.9 | 166.5 | 263.1 | 300.8 | 174.5 | 132.9 | 147.8
White, non-Hispanic^2^ | 14.9 | 17.9 | 19.1 | 26.6 | 19.0 | 14.5 | 14.2
Younger than 25 | 10.5 | 13.1 | 11.5 | 16.9 | 10.8 | 8.4 | 10.0
25–39 | 13.8 | 16.8 | 17.6 | 24.5 | 17.9 | 13.8 | 13.0
40 and older | 72.0 | 75.2 | 96.8 | 126.9 | 83.9 | 56.6 | 58.8
Hispanic | 11.8 | 12.6 | 18.2 | 28.0 | 16.9 | 12.4 | 12.1
Younger than 25 | 7.6 | 8.5 | 7.7 | 14.1 | 9.5 | 10.1 | 11.3
25–39 | 12.4 | 12.2 | 19.2 | 30.8 | 16.9 | 12.0 | 11.2
40 and older | 38.6 | 57.3 | 86.0 | 86.4 | 70.7 | 35.8 | 35.2

* Estimate does not meet National Center for Health Statistics standards of reliability.

^1^Total includes deaths for race and Hispanic-origin groups not shown separately, including women of multiple races and origin not stated.

^2^Race groups are single race.

^3^Maternal mortality rates are deaths per 100,000 live births.

NOTES: Maternal causes are those assigned to categories A34, O00–O95, and O98–O99 of the International Classification of Diseases, 10th Revision. Maternal deaths occur while pregnant or within 42 days of being pregnant. People of Hispanic origin may be of any race.

SOURCES: National Center for Health Statistics, National Vital Statistics System, mortality and natality data files.

In 2024, maternal mortality rates were 13.7 deaths per 100,000 live births for women younger than age 25, 16.5 for those ages 25–39, and 62.3 for those age 40 and older (Figure 3, Table). The rate for women age 40 and older was five times higher than the rate for women younger than age 25. Differences in the rates between women younger than age 25 and ages 25–39 compared with women age 40 and older were significant, while differences between women younger than age 25 and ages 25–39 were not. The observed decrease for women ages 25–39 and the increases for women younger than age 25 and age 40 and older between 2023 and 2024 were not significant.

## Data source and methods

Data are from the NVSS mortality file (3). Consistent with previous reports, the number of maternal deaths does not include all deaths of pregnant women or of recently pregnant women, but only those deaths with the underlying cause of death assigned to International Statistical Classification of Diseases, 10th Revision codes A34, O00–O95, and O98–O99. Maternal mortality rates are per 100,000 live births. Births are based on data from the NVSS natality file. Maternal mortality rates fluctuate from year to year because of the relatively small number of these events, and possibly because of issues with the accuracy of reporting maternal deaths on death certificates (4). Efforts to improve data quality are ongoing, and these data will continue to be evaluated for possible errors. Data are shown for only the largest race and Hispanic-origin groups for which statistically reliable rates can be calculated, and numbers and rates are suppressed for those groups for which statistically reliable rates cannot be calculated (5). Additional details and data on provisional maternal mortality rates are available (6,7).

## References

1 Hoyert DL. Maternal mortality rates in the United States, 2023. NCHS Health E-Stats. 2025 Feb;1–7. DOI: 10.15620/cdc/174577.
2 World Health Organization. International statistical classification of diseases and related health problems, 10th revision. 2008 ed. 2009.
3 Xu JQ, Murphy SL, Kochanek KD, Arias E. Mortality in the United States, 2024. NCHS Data Brief. 2026 Jan;(548):1–14. DOI: 10.15620/cdc/174641.
4 Hoyert DL, Miniño AM. Maternal mortality in the United States: Changes in coding, publication, and data release, 2018. Natl Vital Stat Rep. 2020 Jan 30;69(2):1–18.
5 Xu JQ, Murphy SL, Kochanek KD, Arias E. Deaths: Final data for 2022. Natl Vital Stat Rep. 2025 Jun 10;74(4):1–138. DOI: 10.15620/cdc/174588.
6 National Center for Health Statistics. Maternal mortality. Available from: https://www.cdc.gov/nchs/maternal-mortality/index.htm.
7 National Center for Health Statistics. Provisional maternal mortality rates. Available from: https://www.cdc.gov/nchs/nvss/vsrr/provisional-maternal-deaths-rates.htm.