# Health E-Stat 117 A Decade of Decline in Twin Childbearing in the United States, 2014–2024

### Introduction

This report presents information on trends in twin childbearing by maternal age and race and Hispanic origin from 2014 to 2024.

### Methods

Data are from the National Vital Statistics System birth files. Descriptive statistics are presented on the number of twin births and twin birth rates from 2014 to 2024, and twin births rates by maternal age and maternal race and Hispanic origin for 2014 and 2024.

### Key findings

From 2014 to 2024, the twin birth rate declined 11%, from 33.9 twins per 1,000 births to 30.1. The number of births in twin deliveries declined 19%, from 135,336 in 2014 to 109,195 in 2024, compared with a 9% decline in the number of births in singleton deliveries (3,848,214 to 3,517,151). The largest declines in twinning rates were for mothers age 30 and older and for White non-Hispanic mothers.

The twin birth rate (twin births per 1,000 total births) rose 79% from 1980 (18.9) to 2014 (33.9), then began to decline (1–4). Trends in twin childbearing are of public health interest because of the increased maternal and neonatal risk compared with singleton pregnancies (5–7). This report describes trends in the number and rate of twins born in the United States from the most recent high in 2014 through 2024. It also describes changes in the twin birth rate by maternal age and race and Hispanic origin from 2014 to 2024.

The twin birth rate declined an average 1% per year from 2014 (33.9 twins per 1,000 births) to 2024 (30.1) for a total decline of 11% (Table, Figure 1). The number of births in twin deliveries declined an average 2% per year from 2014 (135,336) to 2024 (109,195) for a total decline of 19%. In comparison, the number of births in singleton deliveries declined 9% (from 3,848,214 to 3,517,151) over the same decade (Table). The largest single-year decline in both the number (7%) and rate (3%) of twin births during 2014–2024 occurred in 2020.

Figure 1 Number and rate of twin births: United States, 2014-2024

NOTES: A significant decreasing trend is shown for 2014 to 2024 for both number (bars) and rate (line), p < 0.05. Rate is the number of twin births per 1,000 total births.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 1 is a combined bar chart showing number of twin births and line graph showing the rate of twin births from 2014 through 2024.

Table

Number of singleton births and number and rate of twin births: United States, 2014–2024

Year | Number of singleton births^1^ | Number of twin births^2^ | Twin birth rate^2,3^
2014 | 3,848,214 | 135,336 | 33.9
2015 | 3,841,219 | 133,155 | 33.5
2016 | 3,810,149 | 131,723 | 33.4
2017 | 3,723,273 | 128,310 | 33.3
2018 | 3,664,651 | 123,536 | 32.6
2019 | 3,623,963 | 120,291 | 32.1
2020 | 3,498,335 | 112,437 | 31.1
2021 | 3,547,198 | 114,161 | 31.2
2022 | 3,550,380 | 114,483 | 31.2
2023 | 3,482,971 | 110,393 | 30.7
2024 | 3,517,151 | 109,195 | 30.1

^1^Significant decreasing trend for 2014 to 2020, p < 0.05.

^2^Significant decreasing trend for 2014 to 2024, p < 0.05.

^3^Twin births per 1,000 total births.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

By maternal age, the largest declines in twinning rates from 2014 to 2024 were for mothers age 30 and older. Those rates were down 18% for mothers ages 30–34 (40.3 to 33.2 per 1,000 births), 27% for mothers 35–39 (48.6 to 35.4), and 46% for mothers 40 and older (66.0 to 35.6) (Figure 2). The rate for mothers ages 25–29 declined 5% (30.5 to 28.9), while changes in rates for mothers 20–24 (23.0 to 22.7) and younger than 20 (16.0 to 16.1) were not significant.

Figure 2 Twin birth rate, by maternal age: United States, 2014 and 2024

NOTES: A significant decline was seen from 2014 to 2024 for each maternal age group except for mothers younger than 20 and ages 2024, p < 0.05. Rate is the number of twin births per 1,000 total births.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 2 is a bar chart showing twin birth rates for 2014 and 2024 by maternal age group, from younger than 20 to 20 to 24, 25 to 29, 30 to 34, 35 to 39, and 40 and older.

Among the three largest race and Hispanic-origin groups, twin birth rates declined 15% for White non-Hispanic (36.7 to 31.3) and 3% for Hispanic (24.1 to 23.4) mothers, and rose 5% for Black non-Hispanic mothers (40.0 to 42.0) (Figure 3).

Figure 3 Twin birth rate, by maternal race and Hispanic origin: United States, 2014 and 2024

NOTES: A significant change was seen from 2014 to 2024 for each race and Hispanic-origin group, p < 0.05. Rate is the number of twin births per 1,000 total births.

SOURCE: National Center for Health Statistics, National Vital Statistics System, natality data file.

Figure 3 is a bar chart of twin birth rates for 2014 and 2024 by maternal race and Hispanic origin, including Black non-Hispanic, White non-Hispanic, and Hispanic.

## Data source and methods

This report is based on birth certificate data from the National Vital Statistics System (NVSS) data files (8).

Twin birth is defined as two fetuses delivered alive or dead at any time in the pregnancy regardless of gestational age, or delivered at different times during the pregnancy. Data for American Indian and Alaska Native non-Hispanic, Asian non-Hispanic, and Native Hawaiian and Other Pacific Islander non-Hispanic are not shown because of revisions to the 1997 Office of Management and Budget standards on classification of race and ethnicity, which resulted in noncomparable data for these groups over the study period (9). References to differences in birth rates indicate that the change is statistically significant at the 0.05 level based on a two-tailed z test. Trends in the number and rate of twin births for Figure 1 were evaluated using the Joinpoint Regression Program (10).

## References

1 Martin JA, Hamilton BE, Osterman MJK. Three decades of twin births in the United States, 1980–2009. NCHS Data Brief. 2012 Jan;(80):1–8.PMID:22617378.22617378
2 Martin JA, Osterman MJK. Is twin childbearing on the decline? Twin births in the United States, 2014– 2018. NCHS Data Brief. 2019 Oct;(351):1–8. PMID:31751205.31751205
3 Horon I, Martin JA. Changes in twin births in the United States, 2019–2021. Natl Vital Stat Rep. 2022 Dec;71(9):1–11. DOI: 10.15620/cdc:121829
4 Osterman MJK, Hamilton BE, Martin JA, Driscoll AK, Valenzuela CP. Births: Final data for 2023. Natl Vital Stat Rep. 2025 Mar;74(1):1–87. DOI: 10.15620/cdc:175204
5 Multifetal gestations: Twin, triplet, and higher-order multifetal pregnancies. ACOG practice bulletin summary, no 231. Obstet Gynecol. 2021 Jun;137(6):1140–3. DOI: 10.1097/AOG.0000000000004398.PMID:34011883.34011883
6 Madar H, Goffinet F, Seco A, Rozenberg P, Dupont C, Deneux-Tharaux C, EPIMOMS (Epidémiologie de la Morbidité Maternelle Sévère) Study Group. Severe acute maternal morbidity in twin compared with singleton pregnancies. Obstet Gynecol. 2019 Jun;133(6):1141–50. DOI: 10.1097/AOG.0000000000003261.31135727
7 Ely DM, Driscoll AK. Infant mortality in the United States, 2023: Data from the period linked birth/infant death file. Natl Vital Stat Rep. 2025 Jun;74(7):1–20. DOI: 10.15620/cdc:174592 40570233
8 National Center for Health Statistics. Vital statistics online data portal. Birth data files. Available from: https://www.cdc.gov/nchs/data_access/VitalStatsOnline.htm.
9 Office of Management and Budget. Revisions to the standards for classification of federal data on race and ethnicity. Fed Regist. 1997;62(210):58782–90.
10 National Cancer Institute. Joinpoint regression program (version 4.8.0.1) [computer software]. 2020.