# Health E-Stat 100 Maternal Mortality Rates in the United States, 2023

### Introduction

This report presents maternal mortality rates in the United States for 2023.

### Methods

Data are from the National Vital Statistics System mortality file. Maternal mortality rates are per 100,000 live births, based on data from the National Vital Statistics System natality file.

### Key findings

The maternal mortality rate for 2023 decreased to 18.6 deaths per 100,000 live births. In 2023, maternal mortality rates decreased significantly for White non-Hispanic and Hispanic women. Rates decreased significantly for women ages 25–39 and age 40 and older between 2022 and 2023.

This report presents maternal mortality rates for 2023 based on data from the National Vital Statistics System. A maternal death is defined by the World Health Organization as “the death of a woman while pregnant or within 42 days of termination of pregnancy, irrespective of the duration and the site of the pregnancy, from any cause related to or aggravated by the pregnancy or its management, but not from accidental or incidental causes” (1). Maternal mortality rates—the number of maternal deaths per 100,000 live births—are shown in this report by age group and race and Hispanic origin.

This report updates a previous one that showed maternal mortality rates for 2018–2022 (2). In 2023, 669 women died of maternal causes in the United States, compared with 817 in 2022 (2) (Figure 1, Table). The maternal mortality rate for 2023 decreased to 18.6 deaths per 100,000 live births, compared with a rate of 22.3 in 2022.

Figure 1 Maternal mortality rate: United States, 2018–2023

^1^Statistically significant change in rate from previous year (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

This is a line graph of the maternal mortality rates for 2018–2023. The rates increase through 2021 and then decrease through 2023.

Table Number of live births and maternal deaths, and maternal mortality rate, by race and Hispanic origin and age: United States, 2018–2023

Race and Hispanic origin and age | 2018 | 2019 | 2020 | 2021 | 2022 | 2023
| Number of live births
Total^1^ | 3,791,712 | 3,747,540 | 3,613,647 | 3,664,292 | 3,667,758 | 3,596,017
Younger than 25 | 907,782 | 877,803 | 825,403 | 797,334 | 784,299 | 759,713
25–39 | 2,756,974 | 2,739,976 | 2,658,445 | 2,731,223 | 2,738,802 | 2,689,250
40 and older | 126,956 | 129,761 | 129,799 | 135,735 | 144,657 | 147,054
Asian, non-Hispanic^2^ | 240,798 | 238,769 | 219,068 | 213,813 | 218,994 | 215,738
Younger than 25 | 16,338 | 15,071 | 12,993 | 11,149 | 11,002 | 10,352
25–39 | 211,331 | 210,177 | 193,139 | 189,405 | 193,025 | 190,128
40 and older | 13,129 | 13,521 | 12,936 | 13,259 | 14,967 | 15,258
Black, non-Hispanic^2^ | 552,029 | 548,075 | 529,811 | 517,889 | 511,439 | 491,494
Younger than 25 | 176,243 | 169,853 | 159,541 | 149,435 | 140,498 | 131,977
25–39 | 358,276 | 360,206 | 351,648 | 349,170 | 349,740 | 337,697
40 and older | 17,510 | 18,016 | 18,622 | 19,284 | 21,201 | 21,820
White, non-Hispanic^2^ | 1,956,413 | 1,915,912 | 1,843,432 | 1,887,656 | 1,840,739 | 1,787,051
Younger than 25 | 391,829 | 374,129 | 348,666 | 336,792 | 324,604 | 309,033
25–39 | 1,504,888 | 1,480,595 | 1,433,839 | 1,486,249 | 1,449,365 | 1,410,849
40 and older | 59,696 | 61,188 | 60,927 | 64,615 | 66,770 | 67,169
Hispanic | 886,210 | 886,467 | 866,713 | 885,916 | 937,421 | 945,200
Younger than 25 | 275,553 | 270,948 | 258,635 | 255,806 | 264,310 | 266,416
25–39 | 579,553 | 584,109 | 576,690 | 597,703 | 637,735 | 642,429
40 and older | 31,104 | 31,410 | 31,388 | 32,407 | 35,376 | 36,355
| Number of maternal deaths
Total^1^ | 658 | 754 | 861 | 1,205 | 817 | 669
Younger than 25 | 96 | 111 | 114 | 163 | 113 | 95
25–39 | 458 | 544 | 607 | 854 | 578 | 486
40 and older | 104 | 98 | 140 | 188 | 126 | 88
Asian, non-Hispanic^2^ | 32 | 33 | 27 | 36 | 29 | 23
Younger than 25 | * | * | * | * | * | *
25–39 | 25 | 28 | 20 | 24 | 21 | 17
40 and older | * | * | * | * | * | *
Black, non-Hispanic^2^ | 206 | 241 | 293 | 362 | 253 | 247
Younger than 25 | 27 | 32 | 46 | 62 | 44 | 37
25–39 | 137 | 179 | 198 | 242 | 172 | 181
40 and older | 42 | 30 | 49 | 58 | 37 | 29
White, non-Hispanic^2^ | 291 | 343 | 352 | 503 | 350 | 259
Younger than 25 | 41 | 49 | 40 | 57 | 35 | 26
25–39 | 207 | 248 | 253 | 364 | 259 | 195
40 and older | 43 | 46 | 59 | 82 | 56 | 38
Hispanic | 105 | 112 | 158 | 248 | 158 | 117
Younger than 25 | 21 | 23 | 20 | 36 | 25 | 27
25–39 | 72 | 71 | 111 | 184 | 108 | 77
40 and older | 12 | 18 | 27 | 28 | 25 | 13
| Maternal mortality rate^3^
Total^1^ | 17.4 | 20.1 | 23.8 | 32.9 | 22.3 | 18.6
Younger than 25 | 10.6 | 12.6 | 13.8 | 20.4 | 14.4 | 12.5
25–39 | 16.6 | 19.9 | 22.8 | 31.3 | 21.1 | 18.1
40 and older | 81.9 | 75.5 | 107.9 | 138.5 | 87.1 | 59.8
Asian, non-Hispanic^2^ | 13.3 | 13.8 | 12.3 | 16.8 | 13.2 | 10.7
Younger than 25 | * | * | * | * | * | *
25–39 | 11.8 | 13.3 | 10.4 | 12.7 | 10.9 | 8.9
40 and older | * | * | * | * | * | *
Black, non-Hispanic^2^ | 37.3 | 44.0 | 55.3 | 69.9 | 49.5 | 50.3
Younger than 25 | 15.3 | 18.8 | 28.8 | 41.5 | 31.3 | 28.0
25–39 | 38.2 | 49.7 | 56.3 | 69.3 | 49.2 | 53.6
40 and older | 239.9 | 166.5 | 263.1 | 300.8 | 174.5 | 132.9
White, non-Hispanic^2^ | 14.9 | 17.9 | 19.1 | 26.6 | 19.0 | 14.5
Younger than 25 | 10.5 | 13.1 | 11.5 | 16.9 | 10.8 | 8.4
25–39 | 13.8 | 16.8 | 17.6 | 24.5 | 17.9 | 13.8
40 and older | 72.0 | 75.2 | 96.8 | 126.9 | 83.9 | 56.6
Hispanic | 11.8 | 12.6 | 18.2 | 28.0 | 16.9 | 12.4
Younger than 25 | 7.6 | 8.5 | 7.7 | 14.1 | 9.5 | 10.1
25–39 | 12.4 | 12.2 | 19.2 | 30.8 | 16.9 | 12.0
40 and older | 38.6 | 57.3 | 86.0 | 86.4 | 70.7 | 35.8

* Estimate does not meet National Center for Health Statistics standards of reliability.

1 Total includes deaths for race and Hispanic-origin groups not shown separately, including women of multiple races and Hispanic origin not stated.

2 Race groups are single race.

3 Maternal mortality rates are deaths per 100,000 live births.

NOTES: Maternal causes are those assigned to codes A34, O00–O95, and O98–O99 of the International Classification of Diseases, 10th Revision. Maternal deaths occur while pregnant or within 42 days of being pregnant. People of Hispanic origin may be of any race.

SOURCES: National Center for Health Statistics, National Vital Statistics System, mortality and natality data files.

In 2023, maternal mortality rates decreased significantly for White non-Hispanic (subsequently, White) and Hispanic women (Figure 2, Table). The observed decrease for Asian non-Hispanic (subsequently, Asian) and increase for Black non-Hispanic (subsequently, Black) women was not statistically significant. In 2023, the maternal mortality rate for Black women was 50.3 deaths per 100,000 live births and was significantly higher than rates for White (14.5), Hispanic (12.4), and Asian (10.7) women.

Figure 2 Maternal mortality rate, by race and Hispanic origin: United States, 2022 and 2023

^1^Statistically significant difference from Black non-Hispanic women (p < 0.05).

^2^Statistically significant decrease in rate from previous year (p < 0.05).

NOTES: Race groups are single race. People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

This is a bar chart of the maternal mortality rates by single race and Hispanic origin. The rates are greater for Black non-Hispanic women compared with White non-Hispanic, Asian non-Hispanic, and Hispanic women. The decrease between 2022 and 2023 is statistically significant for White non-Hispanic and Hispanic women.

Rates decreased significantly for women ages 25–39 and age 40 and older between 2022 and 2023 (Figure 3, Table). Rates in 2023 were 12.5 deaths per 100,000 live births for women younger than age 25, 18.1 for those ages 25–39, and 59.8 for those age 40 and older. The rate for women age 40 and older was nearly five times higher than the rate for women younger than age 25. Differences in the rates between age groups were statistically significant.

Figure 3 Maternal mortality rate, by age: United States, 2022 and 2023

^1^Statistically significant decrease in rate from previous year (p < 0.05).

^2^Statistically significant difference from younger than 25 (p < 0.05).

^3^Statistically significant difference from 40 and older (p < 0.05).

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

This is a bar chart of the maternal mortality rates by age. The rates increase with increasing age. The decrease between 2022 and 2023 is statistically significant for age groups 25–39 and 40 and older.

## Data sources and methods

Data are from the National Vital Statistics System mortality file (3). Consistent with previous reports, the number of maternal deaths does not include all deaths during pregnancy or among recently pregnant women but only those deaths with the underlying cause of death assigned to International Statistical Classification of Diseases, 10th Revision codes A34, O00–O95, and O98–O99. Maternal mortality rates are per 100,000 live births, based on data from the National Vital Statistics System natality file. Maternal mortality rates fluctuate from year to year because of the relatively small number of these events, and possibly because of issues with the accuracy of reporting maternal deaths on death certificates (4). Efforts to improve data quality are ongoing, and these data will continue to be evaluated for possible errors. Data are shown for only the four largest race and Hispanic-origin groups for which statistically reliable rates can be calculated, and numbers and rates are suppressed for those groups for which statistically reliable rates cannot be calculated (5). Additional details and data on provisional maternal mortality rates are available (6,7).

## References

1 World Health Organization. International statistical classification of diseases and related health problems, 10th revision (ICD–10). 2008 ed. 2009.
2 Hoyert DL. Maternal mortality rates in the United States, 2022. NCHS Health E-Stats. 2023. DOI: 10.15620/cdc/152992.
3 Murphy SL, Kochanek KD, Xu JQ, Arias E. Mortality in the United States, 2023. NCHS Data Brief, no 521. Hyattsville, MD: National Center for Health Statistics. 2024. DOI: 10.15620/cdc/170564.
4 Hoyert DL, Miniño AM. Maternal mortality in the United States: Changes in coding, publication, and data release, 2018. National Vital Statistics Reports; vol 69 no 2. Hyattsville, MD: National Center for Health Statistics. 2020.
5 Murphy SL, Kochanek KD, Xu JQ, Arias E. Deaths: Final data for 2021. National Vital Statistics Reports; vol 73 no 8. Hyattsville, MD: National Center for Health Statistics. 2024. DOI: 10.15620/cdc/158787.
6 National Center for Health Statistics. Maternal mortality. Available from: https://www.cdc.gov/nchs/maternal-mortality/index.htm.
7 National Center for Health Statistics. Provisional maternal mortality rates. Available from: https://www.cdc.gov/nchs/nvss/vsrr/provisional-maternal-deaths-rates.htm.