# No. 561 Dietary Supplement Use: United States, August 2021–August 2023

### Introduction

This report presents estimates of any dietary supplement use in the past 30 days and number of dietary supplements taken among youth ages 0–19 years and among adults age 20 and older in the United States during August 2021–August 2023 as well as trends in use from 2013–2014 through August 2021–August 2023.

### Methods

National Health and Nutrition Examination Survey (NHANES) 30-day dietary supplement use questionnaire data were assessed. Analyses accounted for the complex survey design including nonresponse, noncoverage, and differential probability of selection. Variance estimates were computed using Taylor series linearization. Statistical comparisons were performed using linear regression for increasing or decreasing trends or using t tests for comparisons between groups. Trend tests over time were performed using orthogonal polynomial regression with linear and quadratic terms and accounting for the unequal duration and spacing of time between each survey cycle.

### Key Findings

During August 2021–August 2023, 35.7% of youth ages 0–19 years and 60.2% of adults age 20 and older used a dietary supplement in the past 30 days. Two or more dietary supplements were used by 11.3% of youth and 38.7% of adults. Use of two or more dietary supplements increased among youth and adults from 2013–2014 through August 2021–August 2023. Use of any dietary supplement also increased among adults.

Key findings

### Data from the National Health and Nutrition Examination Survey

- During August 2021–August 2023, 35.7% of youth ages 0–19 years and 60.2% of adults age 20 and older used any dietary supplement in the past 30 days.
- Among youth, dietary supplement use was highest among those ages 2–11 years, while among adults, dietary supplement use increased with age.
- Overall, 11.3% of youth used two or more dietary supplements.
- Overall, 38.7% of adults used two or more dietary supplements, and use increased with age.
- Use of two or more dietary supplements increased among youth and adults from 2013–2014 through August 2021–August 2023.

## Introduction

Dietary supplements are commonly used in the United States and contribute considerably to total nutrient intake in the population (1). People take dietary supplements for many reasons, including improving and maintaining health, preventing disease, and targeting specific organ systems such as skeletal or cardiovascular health (2, 3). Dietary supplement use can help lessen nutritional deficiencies but may also lead to intake of nutrients above tolerable upper intake levels (4, 5). This report presents estimates of any dietary supplement use in the past 30 days and the number of dietary supplements taken among youth ages 0–19 years and adults age 20 and older during August 2021–August 2023, as well as trends in usage from 2013–2014 through August 2021–August 2023.

## Dietary supplement use by sex

- Overall, 35.7% of youth ages 0–19 years took any dietary supplement in the past 30 days during August 2021–August 2023. No differences were seen by sex (Figure 1, Table 1).
- Overall, 60.2% of adults age 20 and older took any dietary supplement.
- More women age 20 and older (66.1%) than men (53.9%) took any dietary supplement.

Figure 1 Percentage of youth and adults who used any dietary supplement in past 30 days, by sex: United States, August 2021–August 2023

Figure 1 is a bar chart showing the percentage of youth and adults using any dietary supplement in the past 30 days by sex from August 2021 to August 2023.

Data table for Figure 1 Data table for Figure 1. Percentage of youth and adults who used any dietary supplement in past 30 days, by sex: United States, August 2021–August 2023

Age group and sex | Sample size | Percent | Standard error
Youth (0–19 years) | 1,945 | 35.7 | 2.6
Female | 986 | 35.0 | 2.7
Male | 959 | 36.4 | 2.8
Adults (20 and older) | 4,775 | 60.2 | 1.5
Female^1^ | 2,672 | 66.1 | 1.1
Male | 2,103 | 53.9 | 2.2

1 Significantly different from males in same age group (p < 0.05).

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

## Dietary supplement use by age

- Youth ages 2–11 years were more likely to take any dietary supplement in the past 30 days (41.9%) than youth ages 0–1 (28.6%) or 12–19 (30.1%) (Figure 2, Table 2).
- The percentage of adults taking any dietary supplement increased with age, from 46.3% among those ages 20–39 to 60.3% among those 40–59 to 75.9% among those 60 and older.

Figure 2 Percentage of youth and adults who used any dietary supplement in past 30 days, by age group: United States, August 2021–August 2023

Figure 2 is a bar chart showing the percentage of youth and adults using any dietary supplement in the past 30 days by age group from August 2021 to August 2023.

Data table for Figure 2 Data table for Figure 2. Percentage of youth and adults who used any dietary supplement in past 30 days, by age group: United States, August 2021–August 2023

Age group (years) | Sample size | Percent | Standard error
Youth
0–1^1^ | 184 | 28.6 | 5.6
2–11^2^ | 1,006 | 41.9 | 3.5
12–19 | 755 | 30.1 | 2.1
Adults
20–39 | 1,111 | 46.3 | 2.3
40–59 | 1,326 | 60.3 | 2.2
60 and older^3^ | 2,338 | 75.9 | 1.5

1 Significantly different from ages 2–11 years (p < 0.05).

2 Significantly different from ages 12–19 years (p < 0.05).

3 Significant increasing linear trend by age (p < 0.05).

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

## Two or more dietary supplements

- Among youth, 11.3% used two or more dietary supplements in the past 30 days (Figure 3, Table 3).
- Use of two or more dietary supplements was lower among youth ages 0–1 year (5.9%) than ages 2–11 (13.0%) and 12–19 (10.5%).
- Overall, 38.7% of adults took two or more dietary supplements. The percentage of adults taking two or more dietary supplements increased with age, from 23.4% among those ages 20–39 to 56.4% among those 60 and older.

Figure 3 Number of dietary supplements used by youth and adults in past 30 days, by age group: United States, August 2021–August 2023

Figure 3 is a bar chart showing the percentage of youth and adults using two or more dietary supplements in the past 30 days by age from August 2021 to August 2023.

Data table for Figure 3 Data table for Figure 3. Number of dietary supplements used by youth and adults in past 30 days, by age group: United States, August 2021–August 2023

Number of dietary supplements used and age group | Sample size | Percent | Standard error
Two or more supplements
Youth (0–19 years) | 1,945 | 11.3 | 1.3
0–1^1^ | 184 | 5.9 | 0.9
2–11 | 1,006 | 13.0 | 1.8
12–19 | 755 | 10.5 | 1.4
Adults (20 and older) | 4,775 | 38.7 | 1.5
20–39 | 1,111 | 23.4 | 1.7
40–59 | 1,326 | 38.5 | 2.0
60 and older^2^ | 2,338 | 56.4 | 2.1
Three or more supplements
Adults (20 and older) | 4,775 | 23.9 | 1.1
20–39 | 1,111 | 10.6 | 1.1
40–59 | 1,326 | 23.2 | 1.6
60 and older^2^ | 2,338 | 39.9 | 2.0
Four or more supplements
Adults (20 and older) | 4,775 | 15.4 | 0.8
20–39 | 1,111 | 6.4 | 0.9
40–59 | 1,326 | 14.7 | 1.1
60 and older^2^ | 2,338 | 26.5 | 1.6

1 Significantly different from ages 2–11 and 12–19 years (p < 0.05).

2 Significant increasing linear trend by age (p < 0.05).

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

## Trends

- No significant changes were seen in the use of any dietary supplement in the past 30 days among youth from 2013–2014 through August 2021–August 2023 (Figure 4, Table 4).
- The percentage of youth taking two or more dietary supplements increased from 2013–2014 (6.4%) through August 2021–August 2023 (11.3%).
- The percentage of adults taking any dietary supplement increased from 2013–2014 (53.8%) through August 2021–August 2023 (60.2%).
- The percentage of adults taking two or more dietary supplements increased from 2013–2014 (30.9%) through August 2021–August 2023 (38.7%).

Figure 4 Trends in percentage of youth and adults who used any dietary supplement or two or more dietary supplements in past 30 days: United States, 2013–2014 through August 2021–August 2023

Figure 4 is a four-line chart of trends in the percentage of youth and adults using any or two or more dietary supplements for 2013 and 2014 through August 2021 to August 2023.

Data table for Figure 4 Data table for Figure 4. Trends in percentage of youth and adults who used any dietary supplement or two or more dietary supplements in past 30 days: United States, 2013–2014 through August 2021–August 2023

Age group and survey year | Sample size | Any dietary supplement | | Two or more dietary supplements
| | Percent | Standard error | Percent | Standard error
Youth (0–19 years)
2013–2014 | 4,405 | 33.1 | 1.4 | 6.4 | 0.9
2015–2016 | 4,252 | 34.1 | 2.6 | 8.5 | 1.4
2017–March 2020 | 6,324 | 34.8 | 1.3 | 7.0 | 0.6
August 2021–August 2023 | 1,945 | 35.7 | 2.6 | ^1^11.3 | 1.3
Adults (20 and older)
2013–2014 | 5,767 | 53.8 | 1.4 | 30.9 | 1.3
2015–2016 | 5,717 | 55.9 | 1.6 | 33.4 | 2.1
2017–March 2020 | 9,224 | 58.5 | 0.8 | 35.5 | 0.9
August 2021–August 2023 | 4,775 | ^1^60.2 | 1.5 | ^1^38.7 | 1.5

1 Significant increasing linear trend (p < 0.05).

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 2013–2014 through August 2021–August 2023.

## Summary

Dietary supplement use remains common in the United States. During August 2021–August 2023, 35.7% of youth and 60.2% of adults used any dietary supplement in the past 30 days, and 11.3% of youth and 38.7% of adults used two or more. Among youth, dietary supplement use was most common among those ages 2–11 years. Among adults, dietary supplement use overall increased with age and was more common among women age 20 and older than men. Use of two or more dietary supplements also increased with age among adults. From 2013–2014 through August 2021–August 2023, use of two or more dietary supplements increased among both youth and adults. Use of any dietary supplement also increased among adults.

People often use dietary supplements to meet nutrient needs and support specific health goals. Because of relatively high usage in the population, the Academy of Nutrition and Dietetics stresses the need to watch for overlapping ingredients, potential excesses, and interactions, as well as the need for accessible, evidence-based information for both consumers and healthcare professionals (6).

## Definition

Dietary supplement: A product, other than tobacco, intended to supplement diet and not intended to replace food. Dietary supplements contain vitamins, minerals, herbs or botanicals, amino acids, or other substances. They are intended for ingestion and are labeled as dietary supplements (7). Participants were asked if they had used or taken any vitamins, minerals, herbals, or other dietary supplements in the past 30 days, including prescription and over-the-counter supplements. Participants who answered yes were asked additional information about each dietary supplement taken. Nonprescription antacids intended for use as antacids are not included.

## Data source and methods

The National Health and Nutrition Examination Survey (NHANES) is a cross-sectional survey designed to monitor the health and nutrition of the U.S. civilian noninstitutionalized population using a complex, multistage probability design. Since 1971, NHANES has collected information on dietary supplement use among participants, including 30-day dietary supplement use since 1988 (2). Before August 2021–August 2023, these questions were asked during an in-home interview. During August 2021–August 2023, the questions were asked during a telephone dietary interview following examination in a mobile examination center to minimize in-person interactions to reduce exposure to SARS-CoV-2, the virus that causes COVID-19 (8). Additional details are available on changes to the dietary supplement data collection during August 2021–August 2023 (8).

Analyses for years before August 2021–August 2023 used full sample interview weights to account for nonresponse, noncoverage, and differential probability of selection. Analyses for August 2021–August 2023 used Dietary Day 1 sample weights, which accounted for additional nonresponse to the telephone interview and day of the week of interview. Variance estimates were computed using Taylor series linearization. Statistical testing was performed for increasing or decreasing trends using linear regression and for comparisons between groups using t tests. Trend tests over time were performed using orthogonal polynomial regression with linear and quadratic terms and account for the unequal duration and spacing of time between each survey cycle. All differences were considered statistically significant at a p value of 0.05 unless otherwise noted.

Statistical analyses were performed using R (version 4.4.0) software, including the Survey package (version 4.4-2) (9).

## About the author(s)

Bryan Stierman, Catharine A. Couch, and Suruchi Mishra are with the National Center for Health Statistics, Division of Health and Nutrition Examination Surveys. Jaime J. Gahche is with the National Institutes of Health, Office of Dietary Supplements.

## References

1 Mishra S, Gahche JJ, Ogden CL, Dimeler M, Potischman N, Ahluwalia N. Dietary supplement use in the United States: National Health and Nutrition Examination Survey, 2017–March 2020. Natl Health Stat Report. 2023 Apr;(183):1–14. DOI: https://dx.doi.org/10.15620/cdc:124677.
2 Gahche JJ, Bailey RL, Potischman N, Ershow AG, Herrick KA, Ahluwalia N, et al. Federal monitoring of dietary supplement use in the resident, civilian, noninstitutionalized US population, National Health and Nutrition Examination Survey. J Nutr. 2018 Aug;148(Suppl 2):1436S–44S. DOI: https://doi.org/10.1093/jn/nxy093. PMID: 31105335.
3 Bailey RL, Gahche JJ, Miller PE, Thomas PR, Dwyer JT. Why US adults use dietary supplements. JAMA Intern Med. 2013 Mar;173(5):355–61. DOI: https://doi.org/10.1001/jamainternmed.2013.2299. PMID: 23381623.
4 Bailey RL, Pac SG, Fulgoni VL 3rd, Reidy KC, Catalano PM. Estimation of total usual dietary intakes of pregnant women in the United States. JAMA Netw Open. 2019 Jun;2(6):e195967. DOI: https://doi.org/10.1001/jamanetworkopen.2019.5967. PMID: 31225890.
5 Wallace TC, Frankenfeld CL, Frei B, Shah AV, Yu CR, van Klinken BJ, et al. Multivitamin/multimineral supplement use is associated with increased micronutrient intakes and biomarkers and decreased prevalence of inadequacies and deficiencies in middle-aged and older adults in the United States. J Nutr Gerontol Geriatr. 2019;38(4):307–28. DOI: https://doi.org/10.1080/21551197.2019.1656135. PMID: 31502930.
6 Marra MV, Bailey RL. Position of the Academy of Nutrition and Dietetics: Micronutrient supplementation. J Acad Nutr Diet. 2018 Nov;118(11):2162–73. DOI: https://doi.org/10.1016/j.jand.2018.07.022. PMID: 30366569.
7 Dietary Supplement Health and Education Act of 1994, Pub. L. No. 103-417 (Oct 25, 1994).
8 Stierman B, Mishra S. Changes to dietary supplement and non-prescription antacid data collection during the NHANES August 2021–August 2023 cycle. National Center for Health Statistics. 2025 Mar. Available from: https://wwwn.cdc.gov/nchs/data/Nhanes/Public/2021/Whitepapers/Aug2023-Dietary-Supplement-Mode-Changes-Whitepaper.pdf.
9 Lumley T. Analysis of complex survey samples (Release 4.4-2) [computer software]. 2024.

## National Center for Health Statistics

Carolyn M. Greene, M.D., Acting Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Health and Nutrition Examination Surveys

Alan E. Simon, M.D., Director

Lara J. Akinbami, M.D., Associate Director for Science

For email updates on NCHS publication releases, subscribe online: www.cdc.gov/nchs/updates.

For questions or general information about NCHS:

Tel: 1–800–CDC–INFO (1–800–232–4636) | TTY: 1–888–232–6348

Internet: www.cdc.gov/nchs | Online request form: www.cdc.gov/info

ISSN 1941–4927 Print ed. | ISSN 1941–4935 Online ed.

CS364598