# No. 557 Prevalence of Selected Chronic Conditions Among Adults Age 45 and Older, by Age and Urbanization Level: United States, 2024

### Introduction

This analysis uses 2024 National Health Interview Survey (NHIS) data to describe the percentage of adults age 45 and older who have ever had heart disease, cancer, chronic obstructive pulmonary disease (COPD), or stroke by age group and urbanization level.

### Methods

Point estimates and their corresponding variances were calculated using SAS-callable SUDAAN software to account for the complex sample design of NHIS. Differences between percentages were evaluated using two-sided significant tests at the 0.05 level. Tests for trends over urbanization levels were evaluated using logistic regression.

### Key Findings

In 2024, the prevalence of heart disease increased with decreasing urbanization level, ranging from 9.8% among adults in large central metropolitan areas to 15.2% among adults in nonmetropolitan areas. The prevalence of cancer was over two times higher among adults age 65 and older compared with adults 45–64 overall and for each urbanization level. Just over 10% of adults age 45 and older living in nonmetropolitan areas have COPD. There was variation in the percentage of adults who had a stroke by urbanization level, and the percentage was consistently higher among adults age 65 and older.

Key findings

### Data from the National Health Interview Survey

- For adults age 45 and older and 45–64, heart disease prevalence was highest in nonmetropolitan areas compared with medium and small, large fringe, and large central metropolitan areas.
- Cancer prevalence was lowest in large central metropolitan areas compared with medium and small, large fringe, and nonmetropolitan areas for adults age 45 and older and 45–64.
- For all age groups, chronic obstructive pulmonary disease (COPD) prevalence was highest in nonmetropolitan areas compared with medium and small, large fringe, and large central metropolitan areas.
- Stroke prevalence was higher in nonmetropolitan areas compared with medium and small, large fringe, and large central metropolitan areas for adults 45 and older and 45–64.

## Introduction

Heart disease, cancer, cerebrovascular diseases (stroke), and chronic lower respiratory diseases, including chronic obstructive pulmonary disease (COPD), are consistently among the 10 leading causes of death for U.S. adults (1). Studies have suggested that variations exist in the prevalence of these conditions by age and urbanization level, prompting further exploration into these differences (2, 3). This report uses 2024 National Health Interview Survey (NHIS) data to describe the prevalence of heart disease, cancer, COPD, and stroke among adults age 45 and older by age and urbanization level.

## Heart disease

- In 2024, 11.3% of adults age 45 and older had ever had heart disease (Figure 1, Table 1).
- Among adults age 45 and older, heart disease prevalence was similar between those living in large central metropolitan (9.8%) and large fringe metropolitan (10.1%) areas, increased to 11.8% in medium and small metropolitan areas, and was highest in nonmetropolitan areas (15.2%).
- Among adults ages 45–64, heart disease prevalence was highest in nonmetropolitan areas (9.9%) compared with those in large central metropolitan (5.1%), large fringe metropolitan (4.7%), and medium and small metropolitan (5.9%) areas.
- Among adults age 65 and older, heart disease prevalence was higher among those in nonmetropolitan areas (21.6%) compared with large central metropolitan (17.5%) and large fringe metropolitan (17.6%) areas. Observed differences between medium and small metropolitan (19.1%) and the other areas were not significant.

Figure 1 Percentage of adults age 45 and older who ever had heart disease, by age group and urbanization level: United States, 2024

Figure 1 is a bar graph showing the percentage of adults age 45 and older who ever had heart disease by age group and urbanization level in 2024.

Data table for Figure 1 Data table for Figure 1. Percentage of adults age 45 and older who ever had heart disease, by age group and urbanization level: United States, 2024

Age group and urbanization level | Percent (95% confidence interval) | Standard error
45 and older
Total | 11.3 (10.8‒11.9) | 0.27
Large central metropolitan | ^1,2^9.8 (8.9–10.9) | 0.51
Large fringe metropolitan | ^1,2^10.1 (9.1–11.1) | 0.51
Medium and small metropolitan | ^2^11.8 (10.8–12.9) | 0.53
Nonmetropolitan | 15.2 (13.9–16.6) | 0.69
45‒64^3^
Total | 5.9 (5.4–6.5) | 0.29
Large central metropolitan | ^2^5.1 (4.1–6.1) | 0.49
Large fringe metropolitan | ^2^4.7 (3.7–6.0) | 0.58
Medium and small metropolitan | ^2^5.9 (4.8–7.1) | 0.57
Nonmetropolitan | 9.9 (8.3–11.6) | 0.83
65 and older
Total | 18.7 (17.8–19.7) | 0.47
Large central metropolitan | ^2^17.5 (15.7–19.4) | 0.92
Large fringe metropolitan | ^2^17.6 (15.9–19.4) | 0.90
Medium and small metropolitan | 19.1 (17.3–20.9) | 0.91
Nonmetropolitan | 21.6 (19.6–23.7) | 1.03

1 Significantly different from adults living in medium and small metropolitan areas (p < 0.05).

2 Significantly different from adults living in nonmetropolitan areas (p < 0.05).

3 Significantly different from adults age 65 and older (p < 0.05).

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

## Cancer

- In 2024, 17.3% of adults age 45 and older were ever diagnosed with cancer (Figure 2, Table 2).
- Among adults age 45 and older, cancer prevalence was lowest in large central metropolitan areas (14.8%) compared with those living in large fringe metropolitan (17.6%), medium and small metropolitan (19.1%), and nonmetropolitan (18.3%) areas.
- Similarly, among adults ages 45–64, cancer prevalence was lowest among those in large central metropolitan areas (8.6%) compared with those living in large fringe metropolitan (10.9%), medium and small metropolitan (11.5%), and nonmetropolitan (10.7%) areas.
- Cancer prevalence among adults age 65 and older living in large central metropolitan areas (24.6%) was lower than among those in medium and small metropolitan (28.4%) and nonmetropolitan (27.4%) areas.

Figure 2 Percentage of adults age 45 and older who ever had cancer, by age group and urbanization level: United States, 2024

Figure 2 is a bar graph showing the percentage of adults age 45 and older who ever had cancer by age group and urbanization level in 2024.

Data table for Figure 2 Data table for Figure 2. Percentage of adults age 45 and older who ever had cancer, by age group and urbanization level: United States, 2024

Age group and urbanization level | Percent (95% confidence interval) | Standard error
45 and older
Total | 17.3 (16.7–18.0) | 0.32
Large central metropolitan | ^1–3^14.8 (13.6–16.0) | 0.59
Large fringe metropolitan | 17.6 (16.5–18.7) | 0.55
Medium and small metropolitan | 19.1 (17.8–20.4) | 0.65
Nonmetropolitan | 18.3 (17.1–19.6) | 0.62
45–64^4^
Total | 10.3 (9.6–11.0) | 0.35
Large central metropolitan | ^1–3^8.6 (7.4–10.0) | 0.65
Large fringe metropolitan | 10.9 (9.5–12.3) | 0.70
Medium and small metropolitan | 11.5 (10.2–12.9) | 0.69
Nonmetropolitan | 10.7 (9.3–12.3) | 0.75
65 and older
Total | 26.9 (25.9–27.9) | 0.51
Large central metropolitan | ^2,3^24.6 (22.7–26.6) | 0.98
Large fringe metropolitan | 26.9 (24.9–29.0) | 1.02
Medium and small metropolitan | 28.4 (26.5–30.4) | 1.00
Nonmetropolitan | 27.4 (25.6–29.3) | 0.95

1 Significantly different from adults living in large fringe metropolitan areas (p < 0.05).

2 Significantly different from adults living in medium and small metropolitan areas (p < 0.05).

3 Significantly different from adults living in nonmetropolitan areas (p < 0.05).4Significantly different from adults age 65 and older (p < 0.05).

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

## COPD

- In 2024, 7.0% of adults age 45 and older had ever had COPD (Figure 3, Table 3).
- Among adults age 45 and older, COPD prevalence was highest among those living in nonmetropolitan areas (10.6%) compared with the other areas. COPD prevalence was also higher among those living in medium and small metropolitan areas (7.6%) compared with those in large central metropolitan (5.4%) and large fringe metropolitan (5.8%) areas. Patterns were similar among adults ages 45–64.
- Among adults age 65 and older, COPD prevalence was highest among those living in nonmetropolitan areas (14.0%) compared with those in large central metropolitan (8.5%), large fringe metropolitan (9.2%), and medium and small metropolitan (10.7%) areas. Prevalence was also higher among those in medium and small metropolitan areas compared with large central metropolitan areas.

Figure 3 Percentage of adults age 45 and older who ever had chronic obstructive pulmonary disease, by age group and urbanization level: United States, 2024

Figure 3 is a bar graph showing the percentage of adults age 45 and older who ever had chronic obstructive pulmonary disease by age group and urbanization level in 2024.

Data table for Figure 3 Data table for Figure 3. Percentage of adults age 45 and older who ever had chronic obstructive pulmonary disease, by age group and urbanization level: United States, 2024

Age group and urbanization level | Percent (95% confidence interval) | Standard error
45 and older
Total | 7.0 (6.5–7.4) | 0.22
Large central metropolitan | ^1,2^5.4 (4.7–6.2) | 0.39
Large fringe metropolitan | ^1,2^5.8 (5.0–6.6) | 0.40
Medium and small metropolitan | ^2^7.6 (6.8–8.4) | 0.41
Nonmetropolitan | 10.6 (9.4–11.8) | 0.59
45–64^3^
Total | 4.5 (4.1–5.0) | 0.24
Large central metropolitan | ^1,2^3.5 (2.7–4.3) | 0.40
Large fringe metropolitan | ^1,2^3.4 (2.6–4.4) | 0.44
Medium and small metropolitan | ^2^5.0 (4.1–6.0) | 0.48
Nonmetropolitan | 7.7 (6.5–9.1) | 0.66
65 and older
Total | 10.3 (9.6–11.0) | 0.35
Large central metropolitan | ^1,2^8.5 (7.2–9.9) | 0.67
Large fringe metropolitan | ^2^9.2 (7.8–10.7) | 0.71
Medium and small metropolitan | ^2^10.7 (9.5–12.0) | 0.63
Nonmetropolitan | 14.0 (12.2–15.9) | 0.91

1 Significantly different from adults living in medium and small metropolitan areas (p < 0.05).

2 Significantly different from adults living in nonmetropolitan areas (p < 0.05).

3 Significantly different from adults age 65 and older (p < 0.05).

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

## Stroke

- In 2024, 5.0% of adults age 45 and older had ever had a stroke (Figure 4, Table 4).
- Among adults age 45 and older, stroke prevalence was higher in nonmetropolitan areas (7.1%) compared with the other areas and was lowest in large fringe metropolitan areas (3.8%).
- Among adults ages 45–64, stroke prevalence was highest in nonmetropolitan areas (5.3%) compared with large central metropolitan (2.8%), large fringe metropolitan (1.8%), and medium and small metropolitan (3.2%) areas. Stroke prevalence was lower in large fringe metropolitan areas compared with medium and small metropolitan areas.
- Among adults age 65 and older, stroke prevalence was higher in nonmetropolitan areas (9.3%) compared with large fringe metropolitan (6.5%) and medium and small metropolitan (7.1%) areas. Stroke prevalence in large central metropolitan areas was higher compared with large fringe metropolitan areas.

Figure 4 Percentage of adults age 45 and older who ever had a stroke, by age group and urbanization level: United States, 2024

Figure 4 is a bar graph showing the percentage of adults age 45 and older who ever had a stroke by age group and urbanization level in 2024.

Data table for Figure 4 Data table for Figure 4. Percentage of adults age 45 and older who ever had a stroke, by age group and urbanization level: United States, 2024

Age group and urbanization level | Percent (95% confidence interval) | Standard error
45 and older
Total | 5.0 (4.6–5.4) | 0.19
Large central metropolitan | ^1,2^5.0 (4.3–5.8) | 0.37
Large fringe metropolitan | ^2,3^3.8 (3.2–4.5) | 0.32
Medium and small metropolitan | ^2^5.0 (4.3–5.7) | 0.36
Nonmetropolitan | 7.1 (6.1–8.2) | 0.52
45–64^4^
Total | 3.0 (2.7–3.5) | 0.21
Large central metropolitan | ^2^2.8 (2.1–3.6) | 0.37
Large fringe metropolitan | ^2,3^1.8 (1.3–2.6) | 0.32
Medium and small metropolitan | ^2^3.2 (2.4–4.1) | 0.41
Nonmetropolitan | 5.3 (4.1–6.9) | 0.69
65 and older
Total | 7.7 (7.1–8.3) | 0.32
Large central metropolitan | ^1^8.5 (7.2–9.9) | 0.69
Large fringe metropolitan | ^2^6.5 (5.3–7.8) | 0.62
Medium and small metropolitan | ^2^7.1 (6.0–8.4) | 0.59
Nonmetropolitan | 9.3 (8.0–10.6) | 0.64

1 Significantly different from adults living in large fringe metropolitan areas (p < 0.05).

2 Significantly different from adults living in nonmetropolitan areas (p < 0.05).

3 Significantly different from adults living in medium and small metropolitan areas (p < 0.05).

4 Significantly different from adults age 65 and older (p < 0.05).

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

## Summary

In 2024, 11.3% of U.S. adults age 45 and older had ever had heart disease, 17.3% had cancer, 7.0% had COPD, and 5.0% had a stroke. Overall, adults age 45 and older living in nonmetropolitan areas were more likely to have heart disease, COPD, and stroke compared with those in all other urbanization levels. Adults living in large central metropolitan areas were generally the least likely to have had cancer compared with those in all other urbanization levels, and the prevalence was similar for adults living in nonmetropolitan, medium and small metropolitan, and large fringe metropolitan areas.

## Definitions

Cancer: Based on a “yes” response to the survey question, “Have you ever been told by a doctor or other health professional that you had cancer or a malignancy of any kind?”

Chronic obstructive pulmonary disease (COPD): Based on a “yes” response to the survey question, “Have you ever been told by a doctor or other health professional that you had chronic obstructive pulmonary disease, COPD, emphysema, or chronic bronchitis?”

Heart disease: Based on a “yes” response to one or more of the following survey questions, “Have you ever been told by a doctor or other health professional that you had coronary heart disease?”, “Have you ever been told by a doctor or other health professional that you had angina, also called angina pectoris?”, and “Have you ever been told by a doctor or other health professional that you had a heart attack, also called myocardial infarction?”

Stroke: Based on a “yes” response to the survey question, “Have you ever been told by a doctor or other health professional that you had a stroke?”

Urbanization level: Metropolitan status and size were determined using the 2023 National Center for Health Statistics Urban–Rural Classification Scheme for counties (4). Large metropolitan areas are metropolitan statistical areas of 1 million people or more and are categorized into central and fringe counties. Medium metropolitan areas are counties in metropolitan statistical areas of 250,000–999,999 people, and small metropolitan areas are counties in areas of less than 250,000 people. Nonmetropolitan areas are counties in micropolitan statistical areas and noncore counties.

## Data source and methods

Data from the 2024 NHIS were used for this analysis. NHIS is a nationally representative household survey of the U.S. civilian noninstitutionalized population. It is conducted continuously throughout the year by the National Center for Health Statistics (NCHS). Interviews are typically initiated face-to-face in respondents’ homes, with follow-ups conducted by telephone as needed. For more information on the survey, visit the NHIS website: https://www.cdc.gov/nchs/nhis/index.htm.

Point estimates and their corresponding variances were calculated using SAS-callable SUDAAN software (5) to account for the complex sample design of NHIS. Differences between percentages were evaluated using two-sided significance tests at the 0.05 level. All estimates in this report meet NCHS standards of reliability (6).

## About the author(s)

Xun Wang and Lindsey I. Black are with the National Center for Health Statistics, Division of Health Interview Statistics.

## References

1 Murphy SL, Kochanek KD, Xu J, Arias E. Mortality in the United States, 2023. NCHS Data Brief. 2024 Dec;(521):1–13. PMID: 39819663. DOI: https://dx.doi.org/10.15620/cdc/170564.
2 Watson KB, Wiltz JL, Nhim K, Kaufmann RB, Thomas CW, Greenlund KJ. Trends in multiple chronic conditions among US adults, by life stage, Behavioral Risk Factor Surveillance System, 2013–2023. Prev Chronic Dis. 2025 Apr;22:E15. PMID: 40245168. DOI: https://dx.doi.org/10.5888/pcd22.240539.
3 Moy E, Garcia MC, Bastian B, Rossen LM, Ingram DD, Faul M, et al. Leading causes of death in nonmetropolitan and metropolitan areas—United States, 1999–2014. MMWR Surveill Summ 2017;66(No. SS–1):1–8. PMID: 28081058. DOI: https://dx.doi.org/10.15585/mmwr.ss6601a1.
4 National Center for Health Statistics. NCHS urban–rural classification scheme for counties. 2024. Available from: https://www.cdc.gov/nchs/data-analysis-tools/urban-rural.html.
5 RTI International. SUDAAN (Release 11.0.3) [computer software]. 2018.
6 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. National Center for Health Statistics. Vital Health Stat 2. 2017 Aug;(175):1–22. PMID: 30248016.

## National Center for Health Statistics

Carolyn M. Greene, M.D., Acting Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Health Interview Statistics

Stephen J. Blumberg, Ph.D., Director

Anjel Vahratian, Ph.D., M.P.H., Associate Director for Science

For email updates on NCHS publication releases, subscribe online: www.cdc.gov/nchs/updates.

For questions or general information about NCHS:

Tel: 1–800–CDC–INFO (1–800–232–4636) | TTY: 1–888–232–6348

Internet: www.cdc.gov/nchs | Online request form: www.cdc.gov/info

ISSN 1941–4927 Print ed. | ISSN 1941–4935 Online ed.

CS363886