# No. 545 Diagnosed Allergic Conditions in Adults: United States, 2024

### Introduction

This report uses data from the 2024 National Health Interview Survey (NHIS) to describe the prevalence of diagnosed seasonal allergies, eczema, and food allergies among adults in the United States, by age, sex, race and Hispanic origin, and urbanization level.

### Methods

Point estimates and the corresponding confidence intervals for this analysis were calculated using SAS-callable SUDAAN software to account for the complex sample design of NHIS. Differences between percentages were evaluated using two-sided significance tests at the 0.05 level. Linear and quadratic trends by age group were evaluated using orthogonal polynomials.

### Key Findings

In 2024, 31.7% of adults had a diagnosed seasonal allergy, diagnosed eczema, or a diagnosed food allergy. The percentage of adults with a diagnosed seasonal allergy was higher among those living in nonmetropolitan areas (28.1%) than those living in metropolitan areas (24.8%). Women (9.5%) were more likely to have diagnosed eczema compared with men (5.7%). The prevalence of these selected allergic conditions varied by age group and race and Hispanic origin.

Key findings

### Data from the National Health Interview Survey

- In 2024, 31.7% of adults had a diagnosed seasonal allergy, diagnosed eczema, or a diagnosed food allergy.
- The percentage of adults with a diagnosed seasonal allergy was higher among those living in nonmetropolitan areas than those in metropolitan areas.
- Women were more likely to have diagnosed eczema (9.5%) compared with men (5.7%).
- Diagnosed food allergies were more prevalent in Black non-Hispanic adults (9.9%) compared with Hispanic (5.4%), Asian non-Hispanic (5.5%), and White non-Hispanic (6.4%) adults.

## Introduction

Allergies are common in the U.S. adult population (1). An allergy happens when a person’s immune system overreacts with a specific, reproducible response on exposure to typically harmless substances (2, 3). The severity of allergic reaction symptoms varies and can range from mild symptoms like itchy, watery eyes or hives to serious, life-threatening symptoms like anaphylaxis (2, 4). This report uses data from the 2024 National Health Interview Survey (NHIS) to describe the prevalence of diagnosed seasonal allergies, eczema, and food allergies in adults in the United States by age, sex, race and Hispanic origin, and urbanization level.

## Diagnosed allergic conditions

- In 2024, 31.7% of adults had a diagnosed seasonal allergy (subsequently, seasonal allergy), diagnosed eczema (subsequently, eczema), or a diagnosed food allergy (subsequently, food allergy) (Figure 1, Table 1).
- One-quarter of adults had a seasonal allergy (25.2%), 7.7% had eczema, and 6.7% had a food allergy.

Figure 1 Percentage of adults with a diagnosed seasonal allergy, eczema, food allergy, or any of these allergic conditions: United States, 2024

Figure 1 is a bar chart showing the percentage of adults with a diagnosed seasonal allergy, eczema, food allergy, or any of these allergic conditions in the United States in 2024.

Data table for Figure 1 Data table for Figure 1. Percentage of adults with a diagnosed seasonal allergy, eczema, food allergy, or any of these allergic conditions: United States, 2024

Characteristic | Percent (95% confidence interval) | Standard error
Any allergic condition | 31.7 (31.1–32.4) | 0.34
Seasonal allergy | 25.2 (24.6–25.8) | 0.30
Eczema | 7.7 (7.3–8.0) | 0.19
Food allergy | 6.7 (6.4–7.1) | 0.18

NOTES: Adults were considered to have any allergic condition if they were diagnosed with one or more of three selected conditions: seasonal allergy, eczema, or food allergy. Categories for each allergic condition were not mutually exclusive. Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

## Diagnosed seasonal allergy

- Women were more likely to have a seasonal allergy (29.5%) compared with men (20.7%) (Figure 2, Table 2).
- The prevalence of seasonal allergies increased from 24.3% in adults ages 18–44 to 27.7% in those 45–64, and declined to 25.5% in those 65–74 and 21.7% in those age 75 and older.
- White non-Hispanic (subsequently, White) adults were more likely to have a seasonal allergy (28.5%) compared with Black non-Hispanic (subsequently, Black) (24.4%) Asian non-Hispanic (subsequently, Asian) (17.2%), and Hispanic (16.5%) adults.
- Black adults were more likely to have a seasonal allergy compared with Asian and Hispanic adults.
- Adults living in nonmetropolitan areas were more likely to have a seasonal allergy (28.1%) compared with adults in metropolitan areas (24.8%).

Figure 2 Percentage of adults with a diagnosed seasonal allergy, by sex, age, race and Hispanic origin, and urbanization level: United States, 2024

Figure 2 is a horizontal bar chart showing the percentage of adults with a seasonal allergy by sex, age group, race and Hispanic origin, and urbanization level in the United States in 2024.

Data table for Figure 2 Data table for Figure 2. Percentage of adults with a diagnosed seasonal allergy, by sex, age, race and Hispanic origin, and urbanization level: United States, 2024

Characteristic | Percent (95% confidence interval) | Standard error
Sex
Men | ^1^20.7 (19.9–21.6) | 0.41
Women | 29.5 (28.7–30.3) | 0.43
Age group
18–44 | ^2^24.3 (23.3–25.2) | 0.49
45–64 | 27.7 (26.7–28.8) | 0.52
65–74 | 25.5 (24.2–26.8) | 0.65
75 and older | 21.7 (20.3–23.1) | 0.72
Race and Hispanic origin
Asian, non-Hispanic | ^3,4^17.2 (15.2–19.4) | 1.05
Black, non-Hispanic | ^4,5^24.4 (22.6–26.3) | 0.91
White, non-Hispanic | ^5^28.5 (27.8–29.3) | 0.38
Hispanic | 16.5 (15.3–17.8) | 0.62
Urbanization level
Metropolitan | ^6^24.8 (24.1–25.4) | 0.33
Nonmetropolitan | 28.1 (26.5–29.8) | 0.82

1 Significantly different from women (p < 0.05).

2 Significant quadratic trend by age (p < 0.05).

3 Significantly different from Black non-Hispanic adults (p < 0.05).

4 Significantly different from White non-Hispanic adults (p < 0.05).

5 Significantly different from Hispanic adults (p < 0.05).

6 Significantly different from adults living in nonmetropolitan areas (p < 0.05).

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

## Diagnosed eczema

- Women were more likely to have eczema (9.5%) compared with men (5.7%) (Figure 3, Table 3).
- Adults ages 18–44 were more likely to have eczema (9.1%) than those ages 45–64 (6.8%), 65–74 (6.3%), or 75 and older (5.6%).
- Adults ages 45–64 were more likely than adults age 75 and older to have eczema.
- Black (8.7%), Asian (8.5%), and White (7.9%) adults were more likely to have eczema compared with Hispanic adults (5.1%).
- Adults living in metropolitan areas were more likely to have eczema (7.9%) compared with adults in nonmetropolitan areas (6.4%).

Figure 3 Percentage of adults with diagnosed eczema, by sex, age, race and Hispanic origin, and urbanization level: United States, 2024

Figure 3 is a horizontal bar chart showing the percentage of adults with diagnosed eczema by sex, age group, race and Hispanic origin, and urbanization level in the United States in 2024.

Data table for Figure 3 Data table for Figure 3. Percentage of adults with diagnosed eczema, by sex, age, race and Hispanic origin, and urbanization level: United States, 2024

Characteristic | Percent (95% confidence interval) | Standard error
Sex
Men | ^1^5.7 (5.3–6.2) | 0.24
Women | 9.5 (8.9–10.1) | 0.29
Age group
18–44 | ^2^9.1 (8.4–9.7) | 0.33
45–64 | 6.8 (6.3–7.4) | 0.30
65–74 | 6.3 (5.6–7.1) | 0.39
75 and older | 5.6 (4.9–6.4) | 0.38
Race and Hispanic origin
Asian, non-Hispanic | ^3^8.5 (7.1–10.2) | 0.76
Black, non-Hispanic | ^3^8.7 (7.5–10.1) | 0.66
White, non-Hispanic | ^3^7.9 (7.4–8.4) | 0.24
Hispanic | 5.1 (4.4–5.9) | 0.38
Urbanization level
Metropolitan | ^4^7.9 (7.4–8.3) | 0.22
Nonmetropolitan | 6.4 (5.7–7.2) | 0.37

1 Significantly different from women (p < 0.05).

2 Significant quadratic trend by age (p < 0.05).

3 Significantly different from Hispanic adults (p < 0.05).

4 Significantly different from adults living in nonmetropolitan areas (p < 0.05).

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

## Diagnosed food allergy

- Women were more likely to have a food allergy (8.3%) compared with men (5.1%) (Figure 4, Table 4).
- The percentage of adults with a food allergy decreased with increasing age, from 7.4% in adults ages 18–44 to 4.7% in adults age 75 and older.
- Black adults were more likely to have a food allergy (9.9%) compared with White (6.4%), Asian (5.5%), and Hispanic (5.4%) adults.
- White adults were more likely to have a food allergy compared with Hispanic adults. The observed difference between White and Asian adults was not significant.
- Adults living in metropolitan areas were more likely to have a food allergy (6.8%) compared with adults in nonmetropolitan areas (5.9%).

Figure 4 Percentage of adults with a diagnosed food allergy, by sex, age, race and Hispanic origin, and urbanization level: United States, 2024

Figure 4 is a horizontal bar chart showing the percentage of adults with a diagnosed food allergy by sex, age group, race and Hispanic origin, and urbanization level in the United States in 2024.

Data table for Figure 4 Data table for Figure 4. Percentage of adults with a diagnosed food allergy, by sex, age, race and Hispanic origin, and urbanization level: United States, 2024

Characteristic | Percent (95% confidence interval) | Standard error
Sex
Men | ^1^5.1 (4.6–5.5) | 0.22
Women | 8.3 (7.7–8.8) | 0.28
Age group
18–44 | ^2^7.4 (6.8–8.0) | 0.31
45–64 | 6.8 (6.3–7.4) | 0.29
65–74 | 5.6 (4.9–6.3) | 0.36
75 and older | 4.7 (4.0–5.4) | 0.34
Race and Hispanic origin
Asian, non-Hispanic | ^3^5.5 (4.2–7.1) | 0.71
Black, non-Hispanic | ^4,5^9.9 (8.6–11.4) | 0.68
White, non-Hispanic | ^5^6.4 (6.0–6.9) | 0.21
Hispanic | 5.4 (4.7–6.2) | 0.37
Urbanization level
Metropolitan | ^6^6.8 (6.5–7.2) | 0.20
Nonmetropolitan | 5.9 (5.3–6.6) | 0.33

1 Significantly different from women (p < 0.05).

2 Significant linear trend by age (p < 0.05).

3 Significantly different from Black non-Hispanic adults (p < 0.05).

4 Significantly different from White non-Hispanic adults (p < 0.05).

5 Significantly different from Hispanic adults (p < 0.05).

6 Significantly different from adults living in nonmetropolitan areas (p < 0.05).

NOTE: Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2024.

## Summary

In 2024, 31.7% of adults had a diagnosed seasonal allergy, eczema, or food allergy. One-quarter of adults had a seasonal allergy (25.2%), 7.7% had eczema, and 6.7% had a food allergy. Each of these allergic conditions was higher in women compared with men. While seasonal allergies were higher in nonmetropolitan areas compared with metropolitan areas, eczema and food allergies were higher in metropolitan areas compared with nonmetropolitan areas. The prevalence of these selected allergic conditions varied by age group and race and Hispanic origin.

## Definitions

Any allergic condition: Adults were considered to have any allergic condition if they were diagnosed with one or more of three selected conditions: seasonal allergy, eczema, and food allergy.

Eczema: Based on a positive response to both survey questions, “Do you get an itchy rash due to eczema or atopic dermatitis?” and “Have you ever been told by a doctor or other health professional that you had eczema or atopic dermatitis?”

Food allergy: Based on a positive response to both survey questions, “Do you have an allergy to one or more foods?” and “Have you ever been told by a doctor or other health professional that you had an allergy to one or more foods?”

Race and Hispanic origin: Categories shown for non-Hispanic adults are for those who selected only one racial group; respondents had the option to select more than one racial group. Adults categorized as Hispanic may be of any race or combination of races. Estimates for non­Hispanic adults of races other than Asian, Black, or White are not shown, but are included in total estimates. Analyses were limited to the race and Hispanic-origin groups for which data were reliable and had a large enough sample to make group comparisons.

Seasonal allergy: Based on a positive response to both survey questions, “Do you get symptoms such as sneezing, runny nose, or itchy or watery eyes due to hay fever, seasonal, or year-round allergies?” and “Have you ever been told by a doctor or other health professional that you had hay fever, seasonal, or year-round allergies?”

Urbanization level: Urbanization level was divided into two categories using the 2023 NCHS Urban–Rural Classification Scheme for counties (5): metropolitan (large central metropolitan, large fringe metropolitan, and medium and small metropolitan counties) and nonmetropolitan (counties in micropolitan statistical areas and nonmetropolitan counties).

## Data source and methods

Data from the 2024 NHIS were used for this analysis. NHIS is a nationally representative household survey of the U.S. civilian noninstitutionalized population. It is conducted continuously throughout the year by the National Center for Health Statistics (NCHS). Interviews are typically initiated face-to-face in respondents’ homes with follow-ups conducted by telephone as needed (6). For more information on the survey, visit the NHIS website: https://www.cdc.gov/nchs/nhis/index.htm.

Point estimates and the corresponding confidence intervals for this analysis were calculated using SAS-callable SUDAAN software (7) to account for the complex sample design of NHIS. All estimates are based on self-report and meet NCHS data presentation standards for proportions (8). Differences between percentages were evaluated using two-sided significance tests at the 0.05 level. Linear and quadratic trends by age group were evaluated using orthogonal polynomials.

## About the author(s)

Lauren Bottoms-McClain, Abhigya Giri, and Amanda E. Ng are with the National Center for Health Statistics, Division of Health Interview Statistics.

## References

1 Ng AE, Boersma P. Diagnosed allergic conditions in adults: United States, 2021. NCHS Data Brief. 2023 Jan;(460)1–8. DOI: https://dx.doi.org/10.15620/cdc:122809.
2 O'Hehir RE, Holgate ST, Hershey GK, Sheikh, A, eds. Middleton's allergy essentials. 2nd ed. Elsevier. 2022.
3 Sicherer SH, Sampson HA. Food allergy: A review and update on epidemiology, pathogenesis, diagnosis, prevention, and management. J Allergy Clin Immunol. 2018 Jan;141(1):41–58. PMID: 29157945. DOI: https://doi.org/10.1016/j.jaci.2017.11.003.
4 Asthma and Allergy Foundation of America. Allergy symptoms. Available from: https://aafa.org/allergies/allergy-symptoms/.
5 National Center for Health Statistics. NCHS urban–rural classification scheme for counties. Available from: https://www.cdc.gov/nchs/data-analysis-tools/urban-rural.html.
6 National Center for Health Statistics. National Health Interview Survey: 2024 survey description. 2025. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/NHIS/2024/srvydesc-508.pdf.
7 RTI International. SUDAAN (Release 11.0.3) [computer software]. 2018.
8 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. Vital Health Stat 2. 2017 Aug;(175):1–22.

## National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Health Interview Statistics

Stephen J. Blumberg, Ph.D., Director

Anjel Vahratian, Ph.D., M.P.H., Associate Director for Science

For email updates on NCHS publication releases, subscribe online: www.cdc.gov/nchs/updates/.

For questions or general information about NCHS:

Tel: 1–800–CDC–INFO (1–800–232–4636) | TTY: 1–888–232–6348

Internet: www.cdc.gov/nchs | Online request form: www.cdc.gov/info

ISSN 1941–4927 Print ed. | ISSN 1941–4935 Online ed.

CS362610