# No. 543 Visits to Health Centers by Adults With Attention-Deficit/Hyperactivity Disorder: United States, 2023

### Introduction

This report describes rates and characteristics of health center visits by adults with diagnosed attention-deficit/hyperactivity disorder (ADHD), using data from the 2023 National Ambulatory Medical Care Survey Health Center (NAMCS HC) Component.

### Methods

Data for this report are from the 2023 NAMCS HC Component, and 95 health centers participated out of the 315 health centers that were contacted to participate, resulting in a response rate of 30.2% (unweighted). Data analyses were performed using the statistical packages SAS version 9.4 (SAS Institute, Cary, N.C.) and SAS-callable SUDAAN version 11.0 (RTI International, Research Triangle Park, N.C.). Two-tailed t tests with a significance level of p < 0.05 were used to determine statistically significant differences.

### Key Findings

The health center visit rate for adults with ADHD was 52.6 visits per 10,000 adults in 2023 and decreased by age, with adults with ADHD ages 18–24 having the highest rate (92.6) and those age 65 and older having the lowest rate (6.5). An estimated 69.6% of health center visits by adults with ADHD included documentation in the electronic health record of a co-diagnosis of any of the selected mental health disorders.

Key findings

### Data from the National Ambulatory Medical Care Survey Health Center Component

- The health center visit rate for adults with attention-deficit/hyperactivity disorder (ADHD) was 52.6 visits per 10,000 adults in 2023 and decreased with increasing age.
- Among health center visits by adults with ADHD, most included a co-diagnosis of selected mental health disorders, including anxiety and mood disorders.
- An estimated 40.1% of health center visits by adults with ADHD included a co-diagnosis of selected chronic conditions not related to mental health, including overweight or obesity (24.2% of visits).
- An estimated 41.7% of health center visits by adults with ADHD had a documented amphetamine prescription.

## Introduction

Attention-deficit/hyperactivity disorder (ADHD) is one of the most common childhood disorders and can continue through adolescence into adulthood (1). In 2023, about 15.5 million U.S. adults had an ADHD diagnosis, and more than one-half of those adults were first diagnosed in adulthood (55.9%) (2). Health centers are local, community-based clinics that provide care to those who often encounter issues accessing health care (3). This report describes rates and characteristics of health center visits by adults with diagnosed ADHD, using data from the 2023 National Ambulatory Medical Care Survey Health Center (NAMCS HC) Component (4).

## Visit rates by age

- The health center visit rate for adults with ADHD was 52.6 visits per 10,000 adults in 2023 (Figure 1, Table 1).
- A decreasing trend by age was seen for adults with ADHD, with adults ages 18–24 having the highest rate (92.6) and those age 65 and older having the lowest (6.5).

Figure 1 Visit rate by adults with attention-deficit/hyperactivity disorder at health centers, by age group: United States, 2023

Figure 1 is a bar chart showing the visit rate by adults with ADHD at health centers in 2023 by age group: 18 to 24, 25 to 49, 50 to 64, and 65 and older.

Data table for Figure 1 Visit rate by adults with attention-deficit/hyperactivity disorder at health centers, by age group: United States, 2023

Age group | Percent | 95% confidence interval
Total | 52.6 | 39.3–70.3
18–24 | ^1^92.6 | 68.2–125.8
25–49 | 79.6 | 59.6–106.2
50–64 | 29.5 | 21.1–41.3
65 and older | 6.5 | 4.4–9.8

1 Significant decreasing trend with increasing age (p < 0.05).

NOTES: In 2023, adults age 18 and older with attention-deficit/hyperactivity disorder (ADHD) made 108,590 visits to health centers. For this table, health centers at which all diagnoses were missing for all visits (n = 4) were excluded and visit weights for the remaining health centers were normalized to account for those excluded, representing about 1.4 million health center visits (1.4% of all visits by adults). Visits with ADHD were defined as any visit with an International Classification of Diseases, 10th Revision, Clinical Modification diagnosis code of F90. Visit rates were based on estimates of the U.S. civilian noninstitutionalized population developed by the U.S. Census Bureau. Rates reflect the population as of July 1, 2023.

SOURCE: National Center for Health Statistics, National Ambulatory Medical Care Survey Health Center Component, 2023.

## Co-diagnosis of mental health disorders

- Among health center visits by adults with ADHD, 51.2% had a co-diagnosis of an anxiety disorder, 48.8% a mood disorder, 23.8% a substance use disorder, 6.8% a behavioral syndrome, and 6.5% a personality disorder (Figure 2, Table 2).
- An estimated 69.6% of health center visits by adults with ADHD included documentation in the electronic health record (EHR) of a co-diagnosis of any of the selected mental health disorders.

Figure 2 Co-diagnosis of mental health disorders at health center visits by adults with attention-deficit/hyperactivity disorder: United States, 2023

Figure 2 is a bar chart showing the percentage of adults with ADHD at health center visits with a co-diagnosis of a mental health disorder in 2023.

Data table for Figure 2 Co-diagnosis of mental health disorders at health center visits by adults with attention-deficit/hyperactivity disorder: United States, 2023

Mental health disorder | Percent | 95% confidence interval
Any mental health disorder | 69.6 | 62.1–76.4
Anxiety disorders | 51.2 | 44.3–58.2
Mood disorders | 48.8 | 42.0–55.6
Substance use disorders | 23.8 | 16.8–32.0
Behavioral syndromes | 6.8 | 4.6–9.7
Personality disorders | 6.5 | 4.2–9.5

NOTES: In 2023, adults age 18 and older with attention-deficit/hyperactivity disorder (ADHD) made 108,590 visits to health centers. For this table, health centers at which all diagnoses were missing for all visits (n = 4) were excluded and visit weights for the remaining health centers were normalized to account for those excluded, representing about 1.4 million health center visits (1.4% of all visits by adults). Visits with ADHD were defined as any visit with an International Classification of Diseases, 10th Revision, Clinical Modification (ICD–10–CM) diagnosis code of F90. The “any mental health disorder” category includes only the disorders shown, which were identified using the following ICD–10–CM codes: anxiety disorders, F40–F48; mood disorders, F30–F39; substance use disorders, F10–F19; behavioral syndromes associated with physiological disturbances and physical factors (behavioral syndromes), F50–59; and disorders of adult personality and behavior (personality disorders), F60–F69.

SOURCE: National Center for Health Statistics, National Ambulatory Medical Care Survey Health Center Component, 2023.

## Co-diagnosis of chronic conditions

- Among health center visits by adults with ADHD, 24.2% had a co-diagnosis of overweight or obesity, 13.1% hyperlipidemia, 12.8% hypertension, 11.4% asthma, and 5.4% diabetes (Figure 3, Table 3).
- An estimated 40.1% of health center visits by adults with ADHD included documentation in the EHR of a co-diagnosis of any selected chronic condition not related to mental health.

Figure 3 Co-diagnosis of chronic conditions not related to mental health at health center visits by adults with attention-deficit/hyperactivity disorder: United States, 2023

Figure 3 is a bar chart showing the percentage of adults with ADHD at health center visits with a co-diagnosis of selected chronic conditions in 2023.

Data table for Figure 3 Co-diagnosis of chronic conditions not related to mental health at health center visits by adults with attention-deficit/hyperactivity disorder: United States, 2023

Chronic condition | Percent | 95% confidence interval
Any chronic condition | 40.1 | 33.7–46.9
Overweight or obesity | 24.2 | 19.4–29.4
Hyperlipidemia | 13.1 | 9.7–17.3
Hypertension | 12.8 | 10.0–16.0
Asthma | 11.4 | 8.6–14.9
Diabetes | 5.4 | 3.7–7.6

NOTES: In 2023, adults age 18 and older with attention-deficit/hyperactivity disorder (ADHD) made 108,590 visits to health centers. For this table, health centers at which all diagnoses were missing for all visits (n = 4) were excluded and visit weights for the remaining health centers were normalized to account for those excluded, representing about 1.4 million health center visits (1.4% of all visits by adults). Visits with ADHD were defined as any visit with an International Classification of Diseases, 10th Revision, Clinical Modification (ICD–10–CM) diagnosis code of F90. The “any chronic condition” category includes only the chronic conditions shown, which were identified using the following ICD–10–CM codes: overweight or obesity, E66, Z68.25–Z68.29, Z68.3, Z68.4; hyperlipidemia, E78.0–E78.5; hypertension, H35.00, H35.031, H35.032, H35.033, H35.039, I10–I15, I1A.0–I67.4, N26.2; asthma, J45; and diabetes, E08–E13.

SOURCE: National Center for Health Statistics, National Ambulatory Medical Care Survey Health Center Component, 2023.

## Documented prescriptions

- A prescription for the stimulant medication amphetamine was documented in the EHR at 41.7% of health center visits by adults with ADHD, while the stimulant medication methylphenidate was documented at 8.8% of visits (Figure 4, Table 4).
- A prescription for the nonstimulant medication atomoxetine was documented at 6.0% of health center visits by adults with ADHD, while the nonstimulant medication viloxazine was documented at 0.4% of ADHD visits.
- Among health center visits by adults with ADHD, an estimated 54.6% had a documented prescription for any of the selected ADHD medications.

Figure 4 Percentage of health center visits by adults with attention-deficit/hyperactivity disorder with a documented ADHD medication: United States, 2023

Figure 4 is a bar chart showing the percentage of adults with ADHD at health center visits with a documented ADHD medication in 2023.

Data table for Figure 4 Percentage of health center visits by adults with attention-deficit/hyperactivity disorder with a documented ADHD medication: United States, 2023

ADHD medication | Percent | 95% confidence interval
Any ADHD medication | 54.6 | 44.1–64.8
Stimulants:
Amphetamine | 41.7 | 33.8–50.0
Methylphenidate | 8.8 | 6.8–11.0
Nonstimulants:
Atomoxetine | 6.0 | 4.2–8.3
Viloxazine | 0.4 | 0.2–0.6

NOTES: In 2023, adults age 18 and older with attention-deficit/hyperactivity disorder (ADHD) made 108,590 visits to health centers. For this table, health centers at which all diagnoses and all medications were missing for all visits (n = 20) were excluded and visit weights for the remaining health centers were normalized to account for those excluded, representing about 1.4 million health center visits (1.4% of all visits by adults). Visits with ADHD were defined as any visit with an International Classification of Diseases, 10th Revision, Clinical Modification (ICD–10–CM) diagnosis code of F90. RxNorm concept codes were used to identify stimulant and nonstimulant medications documented in the electronic health record (EHR) for each visit. The “any ADHD medication” category includes only the medications shown. Medications were included if they had an active or completed label in the EHR, and medications with a missing or suspended label were removed. Medications may have been retained in the EHR from a previous visit.

SOURCE: National Center for Health Statistics, National Ambulatory Medical Care Survey Health Center Component, 2023.

## Summary

This report presents nationally representative estimates of health center visits by adults with diagnosed ADHD in the United States during 2023. The overall rate of health center visits among adults with diagnosed ADHD during 2023 was 52.6 visits per 10,000 adults. The health center visit rate for adults with ADHD decreased with age. Almost 70% of the visits by adults with ADHD had any of the selected diagnosed mental health disorders documented in the EHR, including anxiety and mood disorders, and about 40% of visits by adults with ADHD had selected diagnosed chronic conditions not related to mental health documented in the EHR, including overweight or obesity. About 55% of visits by adults with ADHD had at least one documented prescription for an ADHD medication, of which amphetamines were the most common, documented at 41.7% of ADHD visits.

## Definitions

ADHD medications: Includes ADHD medications approved by the Food and Drug Administration for adults (5), categorized as stimulant and nonstimulant medications. Visits with a documented prescription were included when the RxNorm code had an active or completed label in the EHR. Although the medication status of “active” or “complete” indicates that the patient had a prescription for that medication, the prescription could have been given at an earlier visit. The list of RxNorm concept codes used to identify medications was obtained from: https://www.nlm.nih.gov/research/umls/rxnorm/index.html. The “any ADHD medication” category included any of the medications shown in Figure 4, and the amphetamines category included amphetamine, amphetamine-dextroamphetamine, or lisdexamfetamine. Medications were documented in the EHR data using two different coding systems: RxNorm and National Drug Code (NDC). Applying Natural Language Processing techniques, missing medication codes and medications coded in NDC were repopulated by matching the medication name when available with a standardized RxNorm code. This process affected 5.7% of all medication records and resulted in an updated list of RxNorm medications. In this report, only the updated list of RxNorm codes was used to identify ADHD medications. More information is described elsewhere (4).

ADHD visit: All visits that contained an International Classification of Diseases, 10th Revision, Clinical Modification (ICD–10–CM) diagnosis code of F90 are included (6), because the data do not specify a primary diagnosis. Historical diagnoses established before the current visit may also have been included.

Chronic conditions not related to mental health: To identify the top five chronic conditions not related to mental health, 16 conditions were examined from the Office of the Assistant Secretary for Health list of chronic conditions (7) and ICD–10–CM definitions available from the Centers for Medicare & Medicaid Services Chronic Conditions Data Warehouse (8). The 16 conditions are: Alzheimer disease, arthritis, asthma, atrial fibrillation, cancer, chronic kidney disease, chronic obstructive pulmonary disease, chronic viral hepatitis, diabetes, heart failure and nonischemic heart disease, HIV, hyperlipidemia, hypertension, ischemic heart disease, osteoporosis, and stroke or transient ischemic attack. Overweight or obesity was added to the chronic conditions list based on previous studies showing a possible correlation with ADHD (9). The top five chronic conditions are shown in Figure 3, and the “any chronic condition” category includes only those five conditions, which were identified using the following ICD–10–CM codes: overweight or obesity (E66, Z68.25–Z68.29, Z68.3, Z68.4); hyperlipidemia (E78.0–E78.5); hypertension (H35.00, H35.031, H35.032, H35.033, H35.039, I10–I15, I1A.0–I67.4, N26.2,); asthma (J45); and diabetes (E08–E13).

Health center: A local, community-based clinic that provides care to those who often encounter issues accessing health care (3). Health centers treat medical, dental, mental health, substance use, and other health care needs. Staff include doctors, dentists, therapists, social workers, eye doctors, obstetricians/gynecologists, pediatricians, case managers, and other medical staff (3). Both federally qualified health centers, which received Section 330 funding from the Health Resources and Services Administration (HRSA), and health center program look-alikes, which met qualifications but did not receive HRSA program funding (10), were included in the sample.

Mental health disorders: To identify the top five mental health disorders, all mental health disorders identified by ICD–10–CM diagnosis codes F01–F99 were examined, excluding the ICD–10–CM code for ADHD (F90). The top five subcategories of mental health disorders are shown in Figure 2, and the “any mental health disorder” category includes only those five disorders, which were identified using the following ICD–10–CM codes: anxiety disorders (F40–F48); mood disorders (F30–F39); substance use disorders (F10–F19); behavioral syndromes associated with physiological disturbances and physical factors disorders (behavioral disorders) (F50–F59), and disorders of adult personality and behavior (personality disorders) (F60–F69).

Visit rate: Calculated by dividing estimates of visits by the number of the U.S. civilian noninstitutionalized population (11) for the age group.

## Data source and methods

Data for this report are from the 2023 NAMCS HC Component, and 95 health centers participated out of the 315 health centers that were contacted to participate, resulting in a response rate of 30.2% (unweighted). In 2023, 64 health centers were newly recruited, of which 27 responded (42.2%). Additionally, of the 64 health centers that previously participated in 2022, 63 continued participation in 2023 (98.4%). Participating health centers submitted data for all visits that occurred in 2023, which consisted of more than 9 million visits (unweighted). ICD–10–CM diagnosis codes were used to define ADHD, mental health disorders, and chronic conditions. Categories are not mutually exclusive, so the same visit may be represented in multiple categories of mental health disorders, chronic conditions, and ADHD medications. Additional sampling design details for the NAMCS HC Component are described elsewhere (4, 12, 13).

Analyses for this report were conducted using data from the NAMCS HC Component restricted-use data file. A public-use version of this file that does not include medications is available from: https://www.cdc.gov/nchs/namcs/documentation/about-the-data-2023.html#cdc_data_surveillance_section_3-health-center-component (https://www.cdc.gov/nchs/namcs/documentation/about-the-data-2023.html). Count estimates and measures of variance may differ between restricted- and public-use files. Information on accessing the restricted-use data file is available from: https://www.cdc.gov/rdc/restricted-nchs-variables/namcs-nhamcs.html?CDC_AAref_Val=https://www.cdc.gov/rdc/b1datatype/dt1224a.htm. Data analyses were performed using the statistical packages SAS version 9.4 (SAS Institute, Cary, N.C.) and SAS-callable SUDAAN version 11.0 (RTI International, Research Triangle Park, N.C.). Two-tailed t tests with a significance level of p < 0.05 were used to determine statistically significant differences. All estimates presented meet NCHS data presentation standards for proportions and rates (14, 15).

Weighting was conducted to account for sampling probabilities and nonresponse, resulting in nationally representative estimates of health center visits to all states and the District of Columbia (4). For diagnosis and medication variables, in certain instances these data were missing from all visits submitted by some of the participating health centers. In these instances, health centers with complete missingness for variables of interest were excluded from analysis, and the visit weights were normalized to account for their exclusion (4, 12).

## About the author(s)

Jill J. Ashman, Loredana Santo, Zachary J. Peters, Titilayo Okeyode, and Doreen Gidali are with the National Center for Health Statistics, Division of Health Care Statistics.

## References

1 National Institute of Mental Health. Attention-deficit/hyperactivity disorder (ADHD). Available from: https://www.nimh.nih.gov/health/topics/attention-deficit-hyperactivity-disorder-adhd.
2 Staley BS, Robinson LR, Claussen AH, Katz SM, Danielson ML, Summers AD, et al. Attention-deficit/hyperactivity disorder diagnosis, treatment, and telehealth use in adults—National Center for Health Statistics Rapid Surveys System, United States, October–November 2023. MMWR Morb Mortal Wkly Rep. 2024 Oct 10;73(40):890–5. DOI: https://dx.doi.org/10.15585/mmwr.mm7340a1.
3 Health Resources and Services Administration. What is a health center? Available from: https://bphc.hrsa.gov/about-health-center-program/what-health-center.
4 National Center for Health Statistics Research Data Center. National Ambulatory Medical Care Survey Health Center Component: 2023 restricted use file data dictionary. 2025. Available from: https://www.cdc.gov/rdc/data/b1/2023-NAMCS-HC-Component-RDC-Data-Dictionary.pdf.
5 Loskutova N, Callen E, Lutgen C, Nichols S, American Academy of Family Physicians National Research Network. Table 2: FDA approved stimulant medications for adult ADHD. 2019. Available from: https://www.aafp.org/dam/AAFP/documents/patient_care/adhd_toolkit/adhd19-management-table2.pdf; and Table 3: FDA approved non-stimulant medications for adult ADHD. 2019. Available from: https://www.aafp.org/dam/AAFP/documents/patient_care/adhd_toolkit/adhd19-management-table3.pdf.
6 National Center for Health Statistics. International classification of diseases, 10th revision, clinical modification (ICD–10–CM). Available from: https://www.cdc.gov/nchs/icd/icd-10-cm/index.html.
7 Goodman RA, Posner SF, Huang ES, Parekh AK, Koh HK. Defining and measuring chronic conditions: Imperatives for research, policy, program, and practice. Prev Chronic Dis. 2013 Apr 25;10:120239. DOI: https://dx.doi.org/10.5888/pcd10.120239.
8 Centers for Medicare & Medicaid Services. Chronic conditions data warehouse: 30 CCW chronic conditions algorithms and change history. Available from: https://www2.ccwdata.org/web/guest/condition-categories-chronic.
9 Cortese S. The association between ADHD and obesity: Intriguing, progressively more investigated, but still puzzling. Brain Sci. 2019 Sep 27;9(10):256. DOI: https://dx.doi.org/ 10.3390/brainsci9100256. PMID: 31569608; PMCID: PMC6826981.
10 Health Resources and Services Administration. What is a health center program look-alike (LAL)? Available from: https://bphc.hrsa.gov/funding/funding-opportunities/health-center-program-look-alikes.
11 U.S. Census Bureau. Postcensal estimates of the civilian noninstitutionalized population of the United States (estimates from special tabulations developed for the National Center for Health Statistics by the Population Division, U.S. Census Bureau using the July 1, 2023, population estimates). Available from: https://www.census.gov/topics/population.html.
12 Santo L, Peters ZJ, Guluma L, Ashman JJ. Visits to health centers among adults, by selected characteristics: United States, 2022. Natl Health Stat Report. 2024 Oct 22;(211):1–11. DOI: https://dx.doi.org/10.15620/cdc/160502.
13 Williams SN, Ukaigwe J, Ward BW, Okeyode T, Shimizu IM. Sampling procedures for the collection of electronic health record data from federally qualified health centers, 2021–2022 National Ambulatory Medical Care Survey. Vital Health Stat 1. 2023 Jun:(203):1–16. Available from: https://dx.doi.org/10.15620/cdc:127730.
14 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. Vital Health Stat 2. 2017 Aug;(175):1–22. PMID: 30248016.
15 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D. et.al. National Center for Health Statistics data presentation standards for rates and counts. Vital Health Stat 2. 2023 Mar;(200);1–26. DOI: https://dx.doi.org/10.15620/cdc:124368.

## National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Health Care Statistics

Carol J. DeFrances, Ph.D., Director

Alexander Strashny, Ph.D., Associate Director for Science

For email updates on NCHS publication releases, subscribe online: www.cdc.gov/nchs/updates/.

For questions or general information about NCHS:

Tel: 1–800–CDC–INFO (1–800–232–4636) | TTY: 1–888–232–6348

Internet: www.cdc.gov/nchs | Online request form: www.cdc.gov/info

ISSN 1941–4927 Print ed. | ISSN 1941–4935 Online ed.

CS362504