# No. 540 Prevalence of Cardiovascular Disease Risk Factors in Adults: United States, August 2021–August 2023

### Introduction

National Health and Nutrition Examination Survey data were used to determine prevalence estimates for no, one, or two or more cardiovascular disease (CVD) risk factors (uncontrolled high blood pressure, uncontrolled high blood lipids, uncontrolled high mean blood glucose as measured with hemoglobin A1c, and high body mass index) in U.S. adults age 20 and older during August 2021–August 2023. Trends are also presented from 2013–2014 through August 2021–August 2023.

### Methods

All participants age 20 and older with complete CVD risk factor data were included. Pregnant women were excluded. All analyses accounted for the survey’s complex, multistage probability design. For August 2021–August 2023, differences in estimates between subgroups were tested using t tests. Polynomial regression models were used to test for linear and quadratic trends, accounting for unequal spacing and lengths of survey cycles. Statistical significance was set at p < 0.05 level.

### Key findings

During August 2021–August 2023, 36.4% of adults had no CVD risk factors, 34.9% had one, and 28.7% had two or more. The prevalence of two or more CVD risk factors was higher in men than in women. The prevalence of no CVD risk factors decreased with age, and the prevalence of one CVD risk factor increased with age. Adults with family income of 350% or more of the federal poverty level had the highest prevalence of no CVD risk factors and the lowest prevalence of two or more CVD risk factors. From 2013–2014 to August 2021–August 2023, the prevalence of two or more CVD risk factors increased.

Key findings

### Data from the National Health and Nutrition Examination Survey

- During August 2021–August 2023, 36.4% of U.S. adults had no cardiovascular disease (CVD) risk factors, 34.9% had one, and 28.7% had two or more.
- A higher percentage of men (31.7%) than women (25.8%) had two or more CVD risk factors.
- The percentage of adults with no CVD risk factors decreased with age, and the percentage of adults with one CVD risk factor or two or more was higher among older adults.
- The percentage of adults with no CVD risk factors was highest and the percentage of adults with two or more CVD risk factors was lowest among those with family income 350% or more of the federal poverty level.
- From 2013–2014 to August 2021–August 2023, the percentage of adults with two or more CVD risk factors increased.

Heart disease is the leading cause of mortality in the United States (1,2). The American Heart Association’s “Life’s Essential 8” (LE8) is a metric with four behavioral factors and four health factors used to assess cardiovascular health (3,4). Blood pressure, blood lipids, blood glucose, and body mass index (BMI), the four health factors of LE8, are cardiovascular disease (CVD) risk factors. Having a greater number of these CVD risk factors is associated with increased risk of CVD and all-cause mortality (3,5). This report presents prevalence estimates for none, one, or two or more of these CVD risk factors (uncontrolled high blood pressure, uncontrolled high blood lipids, uncontrolled high mean blood glucose as measured with hemoglobin A1c, and high BMI) in U.S. adults during August 2021–August 2023.

## During August 2021–August 2023, just over one-third of adults had no CVD risk factors.

- The percentage of adults with no CVD risk factors was 36.4%; one risk factor, 34.9%; and two or more risk factors, 28.7%, during August 2021–August 2023 (Figure 1, Table 1).
- The percentage of adults with no or one CVD risk factors did not differ between men and women.
- More men (31.7%) than women (25.8%) had two or more CVD risk factors.

Figure 1 Prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older, by sex: United States, August 2021–August 2023

Figure 1. Prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older, by sex: United States, August 2021–August 2023

Data table for Figure 1 Prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older, by sex: United States, August 2021–August 2023

Number of CVD risk factors and sex | Sample size | Percent | Standard error
No CVD risk factors
All | 5,249 | 36.4 | 1.4
Men | 2,396 | 34.9 | 1.0
Women | 2,853 | 37.8 | 2.2
One CVD risk factor
All | 5,249 | 34.9 | 0.9
Men | 2,396 | 33.4 | 1.3
Women | 2,853 | 36.4 | 1.3
Two or more CVD risk factors
All | 5,249 | 28.7 | 1.0
Men | 2,396 | ^1^31.7 | 1.4
Women | 2,853 | 25.8 | 1.5

1 Significantly different from women (p < 0.05).

NOTE: Cardiovascular disease (CVD) risk factors include systolic blood pressure ≥ 130 mm Hg or diastolic blood pressure ≥ 80 mm Hg; non-high-density lipoprotein cholesterol ≥ 190 mg/dL; A1c ≥ 6.5%; and body mass index ≥ 30.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

## The percentage of adults with no CVD risk factors decreased with age, while having one or two or more risk factors was higher among older adults.

- The percentage of adults with no CVD risk factors decreased with age, from 53.7% among adults ages 20–39 to 29.6% among adults ages 40–59 to 24.7% among those age 60 and older (Figure 2, Table 2).
- The percentage of adults with one CVD risk factor increased with age, from 27.0% among adults ages 20–39 to 35.9% among adults ages 40–59 to 42.6% among those age 60 and older.
- The percentage of adults with two or more CVD risk factors was lower in adults ages 20–39 (19.3%) compared with adults ages 40–59 (34.5%) and those age 60 and older (32.7%).

Figure 2 Prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older, by age group: United States, August 2021–August 2023

Figure 2. Prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older, by age group: United States, August 2021–August 2023

Data table for Figure 2 Prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older, by age group: United States, August 2021–August 2023

Number of CVD risk factors and age group | Sample size | Percent | Standard error
No CVD risk factors
20–39 | 1,283 | 53.7 | 2.3
40–59 | 1,542 | 29.6 | 1.6
60 and older | 2,424 | ^1^24.7 | 1.3
One CVD risk factor
20–39 | 1,283 | 27.0 | 1.8
40–59 | 1,542 | 35.9 | 1.4
60 and older | 2,424 | ^2^42.6 | 1.2
Two or more CVD risk factors
20–39 | 1,283 | ^3^19.3 | 1.4
40–59 | 1,542 | 34.5 | 1.2
60 and older | 2,424 | 32.7 | 1.8

1 Significant decreasing linear trend with age (p < 0.05).

2 Significant increasing linear trend with age (p < 0.05).

3 Significantly different from ages 40–59 and 60 and older (p < 0.05).

NOTE: Cardiovascular disease (CVD) risk factors include systolic blood pressure ≥ 130 mm Hg or diastolic blood pressure ≥ 80 mm Hg; non-high-density lipoprotein cholesterol ≥ 190 mg/dL; A1c ≥ 6.5%; and body mass index ≥ 30.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

## The percentage of adults with no CVD risk factors was highest among those with family income 350% or more of the federal poverty level.

- The percentage of adults with no CVD risk factors was higher in adults with family income of 350% or more of the federal poverty level (FPL) (38.9%) compared with adults with family income less than 130% FPL (32.9%) and 130% to 349% FPL (33.3%) (Figure 3, Table 3).
- The percentage of adults with one CVD risk factor did not differ between income groups.
- The percentage of adults with two or more CVD risk factors was lower in adults with family income of 350% FPL or more (24.7%) compared with adults with family income less than 130% FPL (31.3%) and 130% to 349% FPL (32.6%).

Figure 3 Prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older, by family income level: United States, August 2021–August 2023

Figure 3. Prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older, by family income level: United States, August 2021–August 2023

Data table for Figure 3 Prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older, by family income level: United States, August 2021–August 2023

Number of CVD risk factors and family income level | Sample size | Percent | Standard error
No CVD risk factors
Less than 130% FPL | 924 | 32.9 | 2.2
130%–349% FPL | 1,742 | 33.3 | 1.8
350% FPL or more | 1,916 | ^1^38.9 | 2.1
One CVD risk factor
Less than 130% FPL | 924 | 35.7 | 1.6
130%–349% FPL | 1,742 | 34.1 | 1.1
350% FPL or more | 1,916 | 36.4 | 1.5
Two or more CVD risk factors
Less than 130% FPL | 924 | 31.3 | 1.7
130%–349% FPL | 1,742 | 32.6 | 1.4
350% FPL or more | 1,916 | ^1^24.7 | 1.7

1 Significantly different from less than 130% FPL and 130%–349% FPL (p < 0.05).

NOTES: Cardiovascular disease (CVD) risk factors include systolic blood pressure ≥ 130 mm Hg or diastolic blood pressure ≥ 80 mm Hg; non-high-density lipoprotein cholesterol ≥ 190 mg/dL; A1c ≥ 6.5%; and body mass index ≥ 30. Family income is a percentage of the federal poverty level (FPL). Income levels are defined by FPL; 12.8% are missing income information.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

## The age-adjusted percentage of adults with two or more CVD risk factors increased between 2013–2014 and August 2021–August 2023.

- From 2013–2014 to August 2021–August 2023, the age-adjusted percentage of adults with two or more CVD risk factors increased from 23.7% to 28.1% (Figure 4, Table 4).
- Between the two most recent survey cycles, 2017–March 2020 and August 2021–August 2023, a significant decrease was seen in the percentage of adults with one CVD risk factor (from 37.2% to 33.9%), but no change was seen in the percentage of adults with no or two or more CVD risk factors.

Figure 4 Trends in age-adjusted prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older: United States, 2013–2014 through August 2021–August 2023

Figure 4. Trends in age-adjusted prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older: United States, 2013–2014 through August 2021–August 2023

Data table for Figure 4 Trends in age-adjusted prevalence of no, one, or two or more cardiovascular disease risk factors in adults age 20 and older: United States, 2013–2014 through August 2021–August 2023

Survey year | Sample size | No CVD risk factors | | One CVD risk factor | | Two or more CVD risk factors
Survey year | Sample size | Percent | Standard error | Percent | Standard error | Percent | Standard error
2013–2014 | 5,054 | 42.1 | 0.9 | 34.1 | 0.8 | 23.7 | 0.4
2015–2016 | 4,916 | 37.8 | 1.4 | 36.5 | 0.8 | 25.8 | 0.9
2017–March 2020 | 7,026 | 36.1 | 1.3 | 37.2 | 0.8 | 26.7 | 1.2
August 2021–August 2023 | 5,249 | ^1^38.0 | 1.4 | ^1^33.9 | 1.0 | ^2^28.1 | 1.0

1 Significant quadratic trend (p < 0.05).

2 Significant increasing linear trend (p < 0.05).

NOTES: Cardiovascular disease (CVD) risk factors include systolic blood pressure ≥ 130 mm Hg or diastolic blood pressure ≥ 80 mm Hg; non-high-density lipoprotein cholesterol ≥ 190 mg/dL; A1c ≥ 6.5%; and body mass index ≥ 30. Estimates are age adjusted by the direct method to the U.S. Census 2000 population using age groups 20–39, 40–59, and 60 and older.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 2013–2014 through August 2021–August 2023.

## Summary

During August 2021–August 2023, nearly two-thirds of adults in the United States had at least one CVD risk factor (uncontrolled high blood pressure, uncontrolled high blood lipids, uncontrolled high mean blood glucose, or high BMI), and differences were observed by sex, age group, and family income. Men were more likely to have two or more CVD risk factors compared with women. The percentage of adults with two or more CVD risk factors was higher among older age groups. The percentage of adults with no CVD risk factors was highest and the percentage of adults with two or more CVD risk factors was lowest among those in the highest income category. From 2013–2014 to August 2021–August 2023, the percentage of adults with two or more CVD risk factors increased.

Continued monitoring of the prevalence of CVD risk factors will provide information on the cardiovascular health of adults in the United States.

## Definitions

Uncontrolled high blood pressure: A measured systolic blood pressure of 130 mm Hg or more or a diastolic blood pressure of 80 mm Hg or more (6), based on the average of three measurements. People defined as having high blood pressure may or may not have been taking medication to lower their blood pressure.

Uncontrolled high blood lipids: Non-high-density lipoprotein cholesterol greater than or equal to 190 mg/dL (3,7). People defined as having high blood lipids may or may not have been taking cholesterol-lowering medication.

Uncontrolled high mean blood glucose: Hemoglobin A1c greater than or equal to 6.5% (8). People defined as having high blood glucose may or may not have been taking medication to control blood glucose.

High body mass index (BMI): Calculated as weight in kilograms divided by height in meters squared. High BMI is defined as BMI of 30.0 or more, corresponding with the definition of obesity (3,9).

Federal poverty level (FPL): The ratio of annual family income to the federal poverty guidelines, expressed as a percentage. Federal poverty guidelines are defined by the U.S. Department of Health and Human Services to account for inflation, family size, and geographic location (10).

## Data source and methods

The National Health and Nutrition Examination Survey (NHANES) is a cross-sectional, nationally representative sample of the U.S. civilian noninstitutionalized population. NHANES consists of home interviews and health examinations and laboratory tests in mobile examination centers. The sample is selected through a complex, multistage probability design. NHANES was conducted continuously from 1999 through March 2020, when data collection was paused due to the COVID-19 pandemic. In August 2021, NHANES resumed data collection with revised operations and procedures. Details on these changes can be found elsewhere (11).

In the present analysis, data from the August 2021–August 2023 NHANES were used to estimate the prevalence of no, one, and two or more CVD risk factors and to test for differences between subgroups. Four NHANES cycles (2013–2014, 2015–2016, 2017–March 2020, and August 2021–August 2023) were used to assess trends in the prevalence of no, one, and two or more CVD risk factors.

All participants age 20 and older with complete CVD risk factor data (blood pressure, blood lipids, mean blood glucose as measured with hemoglobin A1c, and BMI) were included. Pregnant women were excluded. Prevalence estimates were weighted using phlebotomy (blood draw) sample weights for August 2021–August 2023 and examination sample weights for cycles 2013–2014, 2015–2016, and 2017–March 2020 to account for the survey’s complex, multistage probability design. Sample sizes are unweighted. Standard errors of prevalence estimates were calculated using Taylor series linearization. For August 2021–August 2023, differences in estimates between subgroups were tested using t tests. Polynomial regression models were used to test for linear and quadratic trends, accounting for unequal spacing and lengths of survey cycles. Statistical significance was set at p < 0.05 level. Statistical analyses were conducted using R version 4.4.1 and the R survey package.

## About the author(s)

Catharine A. Couch, Rina Mascarenhas, Bryan Stierman, and Cheryl D. Fryar are with the National Center for Health Statistics, Division of Health and Nutrition Examination Surveys.

## References

1 Ahmad FB, Cisewski JA, Xu JQ, Anderson RN. Provisional mortality data—United States, 2022. MMWR Morb Mortal Wkly Rep. 2023 May 5;72(18):488–92.
2 Curtin SC, Tejada-Vera B, Bastian BA. Deaths: Leading causes for 2022. Natl Vital Stat Rep. 2024 Dec;73(10):1–117. DOI: https://dx.doi.org/10.15620/cdc/164020.
3 Lloyd-Jones DM, Allen NB, Anderson CAM, Black T, Brewer LPC, Foraker RE, et al. Life’s essential 8: Updating and enhancing the American Heart Association’s construct of cardiovascular health: A presidential advisory from the American Heart Association. Circulation. 2022 Aug 2;146(5):e18–e43.
4 Lloyd-Jones DM, Ning H, Labarthe D, Brewer LP, Sharma G, Rosamond W, et al. Status of cardiovascular health in US adults and children using the American Heart Association’s new “life’s essential 8” metrics: Prevalence estimates from the National Health and Nutrition Examination Survey (NHANES), 2013 through 2018. Circulation. 2022 Sep 13;146(11):822–35.
5 Arnett DK, Blumenthal RS, Albert MA, Buroker AB, Goldberger ZD, Hahn EJ, et al. 2019 ACC/AHA guideline on the primary prevention of cardiovascular disease: A report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Circulation. 2019 Sep 10;140(11):e596–e646.
6 Whelton PK, Carey RM, Aronow WS, Casey DE Jr, Collins KJ, Himmelfarb CD, et al. 2017 ACC/AHA/AAPA/ABC/ACPM/AGS/APhA/ASH/ASPC/NMA/PCNA guideline for the prevention, detection, evaluation, and management of high blood pressure in adults: A report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Hypertension. 2018 Jun;71(6):1269–324.
7 Grundy SM, Stone NJ, Bailey AL, Beam C, Birtcher KK, Blumenthal RS, et al. 2018 AHA/ACC/AACVPR/AAPA/ABC/ACPM/ADA/AGS/APhA/ASPC/NLA/PCNA guideline on the management of blood cholesterol: A report of the American College of Cardiology/American Heart Association Task Force on Clinical Practice Guidelines. Circulation. 2019 Jun 18;139(25):e1082–e143.
8 American Diabetes Association Professional Practice Committee. Diagnosis and classification of diabetes: Standards of care in diabetes–2024. Diabetes Care. 2024 Jan 1;47(Suppl 1):s20–s42.
9 Centers for Disease Control and Prevention. BMI: Adult BMI categories. 2024 Mar 19. Available from: https://www.cdc.gov/bmi/adult-calculator/bmi-categories.html.
10 U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation. 2021 poverty guidelines. 2021 Feb. Available from: https://aspe.hhs.gov/2021-poverty-guidelines#guidelines.
11 National Center for Health Statistics. National Health and Nutrition Examination Survey: Brief overview and analytic guidance. NHANES August 2021–August 2023. 2024 Sep 20. Available from: https://wwwn.cdc.gov/nchs/nhanes/continuousnhanes/overviewbrief.aspx?Cycle=2021-2023.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Health and Nutrition Examination Surveys

Alan E. Simon, M.D., Director

Lara J. Akinbami, M.D., Associate Director for Science

For more NCHS Data Briefs, visit: https://www.cdc.gov/nchs/products/databriefs.htm .

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/. For questions or general information about NCHS:

Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info

ISSN 1941–4927 Print ed.

ISSN 1941–4935 Online ed.