# No. 532 Unintentional Fall Deaths in Adults Age 65 and Older: United States, 2023

### Introduction

Adults age 65 and older have higher death rates from unintentional falls than other age groups, and falls are the leading cause of injury-related death in this population.

### Methods

National Vital Statistics System underlying cause-of-death mortality data for 2003–2023 were used in this study of unintentional fall deaths in adults age 65 and older, by sex, age group, and race and Hispanic origin. Unintentional fall deaths were identified using International Classification of Diseases, 10th Revision underlying cause-of-death codes W00–W19. Crude rates (deaths per 100,000 population) were calculated. Pairwise comparisons were conducted using the z test (p < 0.05), and trends were assessed using the Joinpoint Regression Program (Version 5.0.2).

### Key findings

The U.S. rate of unintentional fall deaths for adults age 65 and older was 69.9 per 100,000 population in 2023, with rates varying by state. In 2023, the unintentional fall death rate for adults age 65 and older was higher for men (74.2) compared with women (66.3). Rates for both men and women increased with increasing age. Among adults age 85 and older, White non-Hispanic adults had the highest rate of unintentional fall deaths, and Black non-Hispanic adults had the lowest rate. For both men and women, rates of unintentional fall deaths increased between 2003 and 2023 for adults ages 65–74, 75–84, and 85 and older.

Key findings

### Data from the National Vital Statistics System

- In 2023, the unintentional fall death rate for adults age 65 and older was 69.9 per 100,000 population. Rates for both men and women increased with increasing age.
- The unintentional fall death rate for adults age 65 and older was higher for men (74.2) compared with women (66.3) overall, and for each age group.
- Among adults age 85 and older, White non-Hispanic adults had the highest rate of unintentional fall deaths, and Black non-Hispanic adults had the lowest rate, compared with other race and Hispanic-origin groups.
- Rates of unintentional fall deaths increased between 2003 and 2023 for men and women ages 65–74, 75–84, and 85 and older.
- In 2023, rates of unintentional fall deaths for adults age 65 and older ranged across states from 29.5 in Alabama to 158.4 in Wisconsin.

Falls are the leading cause of injury for adults age 65 and older (1). Older adults have higher death rates from unintentional falls than adults in other age groups. This Data Brief updates a previous report (2), presenting the most recent final data on older adult fall death rates along with trends starting from 2003.

## Men age 65 and older had higher rates of unintentional fall deaths compared with women

- In 2023, the unintentional fall death rate for adults age 65 and older was 69.9 per 100,000 population and was higher for men (74.2) compared with women (66.3) (Figure 1, Table 1).
- For each age group, men had higher rates than women.
- Among adults age 65 and older, rates of unintentional fall deaths were lowest for those ages 65–74 (24.7 and 14.2 for men and women, respectively) and highest for those age 85 and older (373.3 and 319.7, respectively).

Figure 1 Rate of unintentional fall deaths for adults age 65 and older, by sex and age group: United States, 2023

^1^Significantly higher than women, p < 0.05.

^2^Significant increasing trend with increasing age, p < 0.05.

NOTES: The 2023 unintentional fall death rate for all adults age 65 and older was 69.9 deaths per 100,000 population. Unintentional fall deaths are identified using International Classification of Diseases, 10th Revision underlying cause-of-death codes W00–W19.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 1 is a bar chart showing the rate of unintentional fall deaths for adults age 65 and older by sex and age group for 2023.

Data table for Figure 1 Rate of unintentional fall deaths for adults age 65 and older, by sex and age group: United States, 2023

Sex | Total | | 65–74^1^ | | 75–84^1^ | | 85 and older^1^
Sex | Number | Deaths per 100,000 | Number | Deaths per 100,000 | Number | Deaths per 100,000 | Number | Deaths per 100,000
Total | 41,400 | 69.9 | 6,650 | 19.2 | 13,719 | 74.7 | 21,031 | 339.5
Women | 21,523 | 66.3 | 2,612 | 14.2 | 6,407 | 62.8 | 12,504 | 319.7
Men | 19,877 | ^2^74.2 | 4,038 | ^2^24.7 | 7,312 | ^2^89.6 | 8,527 | ^2^373.3

1 Significant increasing trend with increasing age, p < 0.05.

2 Significantly higher than women, p < 0.05.

NOTE: Unintentional fall deaths are identified using International Classification of Diseases, 10th Revision underlying cause-of-death codes W00–W19.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

## Rates of unintentional fall deaths among older adults increased with age for all race and Hispanic-origin groups

- Among adults ages 65–74, Asian non-Hispanic (subsequently, Asian) people had a lower rate (11.1 per 100,000 population) than all other race and Hispanic-origin groups except for Hispanic people (12.5). White non-Hispanic (subsequently, White) people had the highest rate (21.5) of all race and Hispanic-origin groups except for American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native) people (18.7) (Figure 2, Table 2).
- Among adults ages 75–84, Black non-Hispanic (subsequently, Black) people had the lowest rate (35.6), and White (84.7) and American Indian and Alaska Native (67.1) people had the highest rates of unintentional fall deaths.
- Among adults age 85 and older, Black people had the lowest rate (123.9), and White people had the highest rate (395.5). Rates for Asian (174.3), Hispanic (179.2), and American Indian and Alaska Native (202.3) people were not significantly different from each other.
- Among older adults of all race and Hispanic-origin groups, rates of unintentional fall deaths were lowest for those ages 65–74 and greatest for those age 85 and older.

Figure 2 Rate of unintentional fall deaths for adults age 65 and older, by race and Hispanic origin and age group: United States, 2023

^1^Rate lower than all other race and Hispanic-origin groups except Hispanic people, p < 0.05.

^2^Rate higher than all other race and Hispanic-origin groups except American Indian and Alaska Native non-Hispanic people, p < 0.05.

^3^Rate lower than all other race and Hispanic-origin groups, p < 0.05.

^4^Rate higher than all other race and Hispanic-origin groups, p < 0.05.

^5^Significant increasing trend by race and Hispanic origin with increasing age group, p < 0.05.

NOTES: Unintentional fall deaths were identified using International Classification of Diseases, 10th Revision underlying cause-of-death codes W00–W19. Rates for Native Hawaiian or Other Pacific Islander non-Hispanic people are not shown due to small numbers. Misclassification of race and Hispanic origin on death certificates results in underestimation of death rates by as much as 34% for American Indian and Alaska Native non-Hispanic people and 3% for Asian non-Hispanic and Hispanic people. Hispanic people may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 2 is a bar chart showing the rate of unintentional fall deaths for adults age 65 and older by race and Hispanic origin and age group for 2023.

Data table for Figure 2 Rate of unintentional fall deaths for adults age 65 and older, by race and Hispanic origin and age group: United States, 2023

Race and Hispanic origin | Overall (65 and older) | | 65–74^1^ | | 75–84^1^ | | 85 and older^1^
Race and Hispanic origin | Number | Deaths per 100,000 | Number | Deaths per 100,000 | Number | Deaths per 100,000 | Number | Deaths per 100,000
Black, non-Hispanic | 1,666 | 29.3 | 495 | 13.7 | 557 | ^2^35.6 | 614 | ^2^123.9
Asian, non-Hispanic | 1,176 | 39.3 | 197 | ^3^11.1 | 393 | 44.3 | 586 | 174.3
Hispanic | 2,101 | 37.6 | 435 | 12.5 | 711 | 45.3 | 955 | 179.2
American Indian and Alaska Native, non-Hispanic | 183 | 50.2 | 42 | 18.7 | 71 | 67.1 | 70 | 202.3
White, non-Hispanic | 36,062 | 81.9 | 5,427 | ^4^21.5 | 11,910 | ^4^84.7 | 18,725 | ^5^395.5

1 Significant increasing trend by race and Hispanic origin with increasing age group, p < 0.05.

2 Lower than all other race and Hispanic-origin groups, p < 0.05.

3 Lower than all other race and Hispanic-origin groups except Hispanic people, p < 0.05.

4 Higher than all other race and Hispanic-origin groups except American Indian and Alaska Native non-Hispanic people, p < 0.05.

5 Higher than all other race and Hispanic-origin groups, p < 0.05.

NOTES: Unintentional fall deaths are identified using International Classification of Diseases, 10th Revision underlying cause-of-death codes W00–W19. Rates for Native Hawaiian or Other Pacific Islander non-Hispanic people are not shown due to small numbers. Misclassification of race and Hispanic origin on death certificates results in the underestimation of death rates by as much as 34% for American Indian and Alaska Native non-Hispanic people and 3% for Asian non-Hispanic and Hispanic people. Hispanic people may be of any race.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

## Unintentional fall death rates among older adults increased for both men and women from 2003 to 2023

- Among men and women age 65 and older, death rates due to unintentional falls increased for all age groups between 2003 and 2023, with varying rates of change across each group (Figure 3, Table 3).
- Among adults ages 65–74, the rate for men increased from 14.3 per 100,000 population in 2003 to 24.7 in 2023, and the rate for women increased from 8.3 to 14.2.
- Among adults ages 75–84, the rate for men increased from 51.3 in 2003 to 89.6 in 2023, and the rate for women increased from 33.6 to 62.8.
- The greatest increases in rates from 2003 to 2023 for both men and women were among adults age 85 and older. Rates for this age group doubled for men (from 178.3 to 373.3) and increased 2.5 times for women (from 128.5 to 319.7).

Figure 3 Rate of unintentional fall deaths for adults age 65 and older, by year, sex, and age group: United States, 2003–2023

^1^Significant increasing trend from 2003 to 2023, p < 0.05.

^2^Significant increasing trend from 2003 to 2008 and from 2018 to 2023 at varying rates of change, p < 0.05.

^3^Significant increasing trend from 2003 to 2012, p < 0.05.

^4^Significant increasing trend from 2014 to 2023, p < 0.05.

^5^Significant increasing trend from 2003 to 2007 and from 2017 to 2021 at varying rates of change, p < 0.05.

NOTE: Unintentional fall deaths are identified using International Classification of Diseases, 10th Revision underlying cause-of-death codes W00–W19.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 3 is a line chart showing the rate of unintentional fall deaths for adults age 65 and older by year, sex, and age group from 2003 to 2023.

Data table for Figure 3 Rate of unintentional fall deaths for adults age 65 and older, by year, sex, and age group: United States, 2003–2023

Year | Women | | | | | | Men
Year | 65–74^1^ | | 75–84^2^ | | 85 and older^3^ | | 65–74^4^ | | 75–84^5^ | | 85 and older^3^
| Number | Deaths per 100,000 | Number | Deaths per 100,000 | Number | Deaths per 100,000 | Number | Deaths per 100,000 | Number | Deaths per 100,000 | Number | Deaths per 100,000
2003 | 839 | 8.3 | 2,588 | 33.6 | 4,018 | 128.5 | 1,209 | 14.3 | 2,661 | 51.3 | 2,386 | 178.3
2004 | 861 | 8.5 | 2,824 | 36.5 | 4,332 | 136.8 | 1,394 | 16.3 | 2,858 | 54.4 | 2,630 | 190.7
2005 | 935 | 9.2 | 2,906 | 37.5 | 4,722 | 145.3 | 1,384 | 15.9 | 3,051 | 57.3 | 2,804 | 194.2
2006 | 961 | 9.3 | 3,080 | 39.8 | 4,973 | 148.6 | 1,431 | 16.2 | 3,147 | 58.7 | 3,058 | 201.4
2007 | 1,012 | 9.6 | 3,221 | 41.9 | 5,693 | 165.2 | 1,582 | 17.4 | 3,331 | 61.8 | 3,495 | 219.4
2008 | 1,101 | 10.0 | 3,443 | 45.0 | 6,088 | 172.3 | 1,644 | 17.3 | 3,564 | 65.8 | 3,902 | 234.7
2009 | 1,119 | 9.8 | 3,304 | 43.5 | 6,512 | 179.3 | 1,731 | 17.6 | 3,682 | 67.8 | 4,074 | 234.8
2010 | 1,212 | 10.4 | 3,570 | 47.1 | 7,029 | 189.8 | 1,776 | 17.6 | 3,679 | 67.2 | 4,383 | 244.9
2011 | 1,223 | 10.2 | 3,552 | 46.7 | 7,655 | 199.2 | 1,926 | 18.4 | 3,835 | 68.8 | 4,710 | 248.7
2012 | 1,336 | 10.5 | 3,864 | 50.7 | 8,039 | 204.9 | 1,996 | 17.8 | 3,912 | 69.3 | 5,043 | 256.8
2013 | 1,402 | 10.4 | 3,811 | 49.6 | 8,488 | 212.3 | 2,184 | 18.5 | 4,175 | 72.5 | 5,404 | 264.7
2014 | 1,556 | 11.1 | 3,940 | 50.6 | 9,057 | 223.4 | 2,382 | 19.3 | 4,317 | 73.3 | 5,792 | 274.6
2015 | 1,577 | 10.8 | 4,102 | 51.9 | 9,501 | 231.0 | 2,514 | 19.5 | 4,566 | 75.8 | 6,226 | 286.3
2016 | 1,752 | 11.5 | 4,193 | 52.0 | 10,002 | 240.7 | 2,727 | 20.4 | 4,542 | 73.5 | 6,452 | 290.0
2017 | 1,815 | 11.5 | 4,292 | 51.7 | 10,433 | 249.1 | 2,937 | 21.2 | 4,926 | 76.9 | 6,787 | 297.7
2018 | 1,992 | 12.3 | 4,551 | 52.6 | 10,706 | 253.8 | 3,118 | 21.9 | 5,158 | 76.6 | 6,997 | 300.9
2019 | 2,102 | 12.5 | 4,915 | 54.8 | 10,864 | 256.9 | 3,286 | 22.4 | 5,650 | 80.7 | 7,395 | 311.2
2020 | 2,318 | 13.3 | 5,280 | 57.2 | 11,449 | 269.8 | 3,607 | 23.8 | 5,896 | 81.6 | 7,958 | 329.6
2021 | 2,520 | 14.2 | 5,708 | 63.2 | 11,900 | 313.2 | 3,889 | 24.5 | 6,428 | 89.7 | 8,297 | 381.3
2022 | 2,570 | 14.4 | 6,258 | 64.0 | 12,372 | 294.4 | 4,128 | 25.9 | 7,138 | 92.3 | 8,453 | 370.1
2023 | 2,612 | 14.2 | 6,407 | 62.8 | 12,504 | 319.7 | 4,038 | 24.7 | 7,312 | 89.6 | 8,527 | 373.3

1 Significant increasing trend from 2003 to 2007 and from 2017 to 2021 at varying rates of change, p < 0.05.

2 Significant increasing trend from 2003 to 2012, p < 0.05.

3 Significant increasing trend from 2003 to 2023, p < 0.05.

4 Significant increasing trend from 2014 to 2023, p < 0.05.

:5 Significant increasing trend from 2003 to 2008, and from 2018 to 2023 at varying rates of change, p < 0.05.

NOTE: Unintentional fall deaths are identified using International Classification of Diseases, 10th Revision underlying cause-of-death codes W00–W19.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

## In 2023, rates of unintentional fall deaths for adults age 65 and older varied by state

- The rate of unintentional fall deaths among adults age 65 and older ranged across states from a low of 29.5 in Alabama to a high of 158.4 in Wisconsin per 100,000 population (Figure 4, Table 4).
- The five states with the highest rates were Wisconsin (158.4), Minnesota (132.6), Maine (126.5), Oklahoma (122.2), and Vermont (120.9).
- The five states with the lowest rates were Alabama (29.5), New Jersey (34.6), California, (40.0), Louisiana (45.6), and Georgia (45.9).

Figure 4 Rate of unintentional fall deaths for adults age 65 and older, by state of residence: United States, 2023

NOTE: Unintentional fall deaths are identified using International Classification of Diseases, 10th Revision underlying cause-of-death codes W00–W19.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

Figure 4 is a map of the United States showing the rate of unintentional fall deaths for adults age 65 and older by state of residence for 2023.

Data table for Figure 4 Rate of unintentional fall deaths for adults age 65 and older, by state of residence: United States, 2023

Area | Number | Deaths per 100,000
United States | 41,400 | 69.9
Alabama | 275 | 29.5
Alaska | 59 | 56.0
Arizona | 1,136 | 79.2
Arkansas | 314 | 57.0
California | 2,523 | 40.0
Colorado | 936 | 99.3
Connecticut | 423 | 61.2
Delaware | 108 | 49.2
District of Columbia | 56 | 63.1
Florida | 4,045 | 82.3
Georgia | 778 | 45.9
Hawaii | 158 | 52.2
Idaho | 341 | 100.0
Illinois | 1,252 | 56.8
Indiana | 687 | 58.3
Iowa | 677 | 113.6
Kansas | 425 | 82.8
Kentucky | 415 | 51.4
Louisiana | 362 | 45.6
Maine | 406 | 126.5
Maryland | 756 | 70.9
Massachusetts | 1,091 | 84.3
Michigan | 1,392 | 72.2
Minnesota | 1,357 | 132.6
Mississippi | 337 | 65.1
Missouri | 731 | 64.3
Montana | 183 | 78.9
Nebraska | 200 | 58.9
Nevada | 378 | 68.0
New Hampshire | 303 | 103.9
New Jersey | 570 | 34.6
New Mexico | 253 | 60.4
New York | 1,759 | 48.4
North Carolina | 1,776 | 93.1
North Dakota | 98 | 73.5
Ohio | 1,920 | 86.9
Oklahoma | 823 | 122.2
Oregon | 884 | 106.6
Pennsylvania | 2,054 | 79.1
Rhode Island | 233 | 110.1
South Carolina | 725 | 69.9
South Dakota | 165 | 97.7
Tennessee | 1,008 | 81.2
Texas | 2,192 | 52.3
Utah | 331 | 79.4
Vermont | 173 | 120.9
Virginia | 1,009 | 67.3
Washington | 1,147 | 85.7
West Virginia | 306 | 80.4
Wisconsin | 1,790 | 158.4
Wyoming | 80 | 71.5

NOTE: Unintentional fall deaths are identified using International Classification of Diseases, 10th Revision underlying cause-of-death codes W00–W19.

SOURCE: National Center for Health Statistics, National Vital Statistics System, mortality data file.

## Summary

In 2023, the national rate of unintentional fall deaths for adults age 65 and older was 69.9 deaths per 100,000 population. Men had higher death rates than women across all older adult age groups, and rates increased with age for both sexes in 2023. The ratio of rates for men compared with women was largest for adults ages 65–74 and narrowed with increasing age, even as overall rates increased by age group for both men and women.

Fall death rates varied by race and Hispanic origin in 2023. Among adults ages 65–74, Asian people had the lowest rates, although the difference between Hispanic and Asian people was not statistically significant, and for adults ages 75–84 and 85 and older, Black people had the lowest rates. The highest rates among people ages 65–74, 75–84, and 85 and older were for White people, although the difference in rates between White and American Indian and Alaska Native people were not statistically significant for the 65–74 and 75–84 age groups.

Rates of unintentional fall deaths increased for all older adult age groups between 2003 and 2023 and were highest among those age 85 and older. Both men and women experienced increasing rates in this period, although at varying rates of change. Rates varied widely across the United States: Wisconsin had the highest rate (158.4), five times greater than Alabama (29.5), which had the lowest rate.

## Data source and methods

National Vital Statistics System underlying cause-of-death mortality data for 2003–2023 were used to study unintentional fall deaths for adults age 65 and older by sex, age group, and race and Hispanic origin (3,4). Unintentional fall deaths were identified using International Classification of Diseases, 10th Revision underlying cause-of-death codes W00–W19 (5). Rates for Native Hawaiian or Other Pacific Islander non-Hispanic people are not reported because of small numbers and unstable rates.

Crude rates (deaths per 100,000 population) were calculated. Pairwise comparisons of rates (such as crude rates for men compared with those for women) were conducted using a z test with an alpha level of 0.05 (two-sided) (6). Statistically significant differences between rates based on fewer than 100 deaths and other rates were determined by comparing 95% confidence intervals of the rates for the two groups. Trends in death rates were evaluated using the Joinpoint Regression Program (Version 5.0.2) (7). Joinpoint software fitted weighted least-squares regression models to the rates on the log-transformation scale. The permutation tests for model (number of joinpoints) significance were set at an overall alpha level of 0.05 (8).

Race and Hispanic origin were categorized based on the Office of Management and Budget’s 1997 standards for federal statistical and administrative reporting (9). All race categories are single race, meaning that only one race was reported on the death certificate. Data shown for Hispanic people include people of any race. Misclassification of race and Hispanic origin on death certificates results in the underestimation of death rates by as much as 34% for American Indian and Alaska Native people and 3% for Asian and Hispanic people (10,11).

## About the authors

Matthew F. Garnett, Julie D. Weeks, and Anne M. Zehner are with the National Center for Health Statistics, Division of Analysis and Epidemiology.

## References

1 National Center for Health Statistics. Mortality data on CDC WONDER: All ages deaths by underlying cause. Available from: https://wonder.cdc.gov/deaths-by-underlying-cause.html.
2 Garnett MF, Weeks JD, Spencer MR. Unintentional fall deaths among adults aged 65 and over: United States, 2020. NCHS Data Brief. 2022 Nov;(449):1–8. DOI: 10.15620/cdc:121836.
3 National Center for Health Statistics, CDC WONDER: Underlying cause of death 1999–2020. 2021. Available from: https://wonder.cdc.gov/deaths-by-underlying-cause.html.
4 National Center for Health Statistics, CDC WONDER: Underlying cause of death 2018–2023. 2025. Available from: https://wonder.cdc.gov/deaths-by-underlying-cause.html.
5 World Health Organization. International statistical classification of diseases and related health problems, 10th revision (ICD–10). 5th ed. 2016.
6 Murphy SL, Kochanek KD, Xu JQ, Arias E. Deaths: Final data for 2021. Natl Vital Stat Rep. 2024 Oct;73(8):1–139. DOI: 10.15620/cdc/158787.
7 National Cancer Institute. Joinpoint Regression Program (Version 5.0.2) [computer software]. 2023.
8 Ingram DD, Malec DJ, Makuc DM, Kruszon-Moran D, Gindi RM, Albert M, et al. National Center for Health Statistics guidelines for analysis of trends. Vital Health Stat 2. 2018 Apr;(179):1–71. PMID: 29775435.
9 Office of Management and Budget. Revisions to the standards for the classification of federal data on race and ethnicity. Fed Regist. 1997 Oct 30;62(210):58782–90.
10 Arias E, Heron M, Hakes J. The validity of race and Hispanic-origin reporting on death certificates in the United States: An update. Vital Health Stat 2. 2016 Aug 1;(172):1–21. PMID: 28436642.
11 Arias E, Xu JQ, Curtin S, Bastian B, Tejada-Vera B. Mortality profile of the non-Hispanic American Indian or Alaska Native population, 2019. Natl Vital Stat Rep. 2021 Nov;70(12):1–27. National Center for Health Statistics. 2021. DOI: 10.15620/cdc:110370.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Analysis and Epidemiology

Irma E. Arispe, Ph.D., Director

Kimberly A. Lochner, Sc.D., Associate Director for Science

For more NCHS Data Briefs, visit:https://www.cdc.gov/nchs/products/databriefs.htm.

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/.

For questions or general information about NCHS: Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info

ISSN 1941–4927 Print ed.

ISSN 1941–4935 Online ed.