# No. 528 Characteristics of Adults Age 18 and Older Who Took Prescription Medication for Depression: United States, 2023

### Introduction

This report uses the most recent National Health Interview Survey data on the use of prescription medication for depression and explores differences in use of medication for depression by age, sex, race and Hispanic origin, disability status, living alone, family income, education level, region, and urbanization level among U.S. adults in 2023.

### Methods

Data from the 2023 National Health Interview Survey were used for this analysis. Point estimates and corresponding variances were calculated using SAS-callable SUDAAN software version 11.0 to account for the survey’s complex sample design. All estimates are based on self-report and meet NCHS data presentation standards for proportions. Differences between percentages were evaluated using two-sided significance tests at the 0.05 level. Linear and quadratic trends by age group and family income were evaluated using orthogonal polynomials in logistic regression.

### Key findings

In 2023, the percentage of adults age 18 and older who took prescription medication for depression was 11.4%; women were more than twice as likely to take medication for depression than men. White non-Hispanic adults and adults of other and multiple races non-Hispanic were more likely to take medication for depression compared with all other race and Hispanic-origin groups. Adults with disabilities were nearly three times as likely to take medication for depression than adults without disabilities. Taking medication for depression decreased with increasing family income. The percentage of adults taking medication for depression was higher in the Midwest compared to other regions and increased with decreasing urbanization level.

Key findings

### Data from the National Health Interview Survey

- In 2023, the percentage of adults age 18 and older who took prescription medication for depression was 11.4%. Women (15.3%) were more than twice as likely to take medication for depression than men (7.4%).
- White non-Hispanic adults and adults who are multiple races were more likely to take medication for depression compared with all other race and Hispanic-origin groups.
- Adults with disabilities (28.2%) were nearly three times as likely to take medication for depression than adults without disabilities (9.7%).
- Taking medication for depression decreased with increasing family income.
- The percentage of adults taking medication for depression was higher in the Midwest compared with other regions and increased with decreasing urbanization level.

Depression is among the most common mental disorders in the United States (1). Treatment for depression typically includes antidepressant medications, psychotherapy, or a combination of both (2). This report uses the most recent National Health Interview Survey (NHIS) data on the use of prescription medication for depression and explores differences in the use of medication for depression by age, sex, race and Hispanic origin, disability status, living arrangement, family income, education level, region, and urbanization level among U.S. adults in 2023.

## What percentage of adults took medication for depression and were there differences by sex and age?

- In 2023, the percentage of adults who took prescription medication for depression was 11.4%. Women (15.3%) were more likely than men (7.4%) to take medication for depression (Figure 1, Table 1).
- Adults ages 18–44 were less likely to take medication for depression (10.7%) than those ages 45–64 (12.1%) or 65–74 (12.4%), but no significant difference was seen between those age 75 and older (11.3%) and any other age group.

Figure 1 Percentage of adults age 18 and older who took medication for depression, by sex and age: United States, 2023

^1^Significantly different from women (p < 0.05).

^2^Significant quadratic trend by age (p < 0.05).

NOTES: Data are based on a yes response to the survey question, “Do you take prescription medication for depression?” Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2023.

Figure 1 is a bar chart showing the percentage of adults age 18 and older who took medication for depression by sex and age in the United States in 2023.

Data table for Figure 1 Percentage of adults age 18 and older who took medication for depression, by sex and age: United States, 2023

Selected characteristic | Percent (95% confidence interval) | Standard error
Total | 11.4 (11.0–11.9) | 0.2
Sex
Men | 7.4 (6.9–7.9) | 0.3
Women | 15.3 (14.7–16.1) | 0.4
Age group (years)
18–44 | 10.7 (10.0–11.4) | 0.4
45–64 | 12.1 (11.4–12.9) | 0.4
65–74 | 12.4 (11.4–13.5) | 0.5
75 and older | 11.3 (10.2–12.6) | 0.6

NOTES: Data are based on a yes response to the survey question, “Do you take prescription medication for depression?” Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2023.

## Did the percentage of adults taking medication for depression vary by race and Hispanic origin, disability status, and living arrangement?

- White non-Hispanic (subsequently, White) adults and adults who are other and multiple races non-Hispanic (subsequently, other and multiple races) were more likely to take prescription medication for depression (14.3% and 14.2%, respectively) than Black non-Hispanic (subsequently, Black) (7.7%), American Indian and Alaska Native non-Hispanic (subsequently, American Indian and Alaska Native) (6.9%), Hispanic (6.7%), and Asian non-Hispanic (subsequently, Asian) (3.4%) adults (Figure 2, Table 2). With the exception of American Indian and Alaska Native adults, Asian adults were less likely than all other race and Hispanic-origin groups to take medication for depression.
- Adults with disabilities were nearly three times as likely to take medication for depression (28.2%) as those without disabilities (9.7%).
- Adults living alone were more likely to take medication for depression (14.4%) compared with adults living with others (10.9%).

Figure 2 Percentage of adults age 18 and older who took medication for depression, by race and Hispanic origin, disability status, and living arrangement: United States, 2023

^1^Significantly different from White non-Hispanic adults (p < 0.05).

^2^Significantly different from other and multiple races non-Hispanic adults (p < 0.05).

^3^Significantly different from Black non-Hispanic adults (p < 0.05).

^4^Significantly different from Hispanic or Latino adults (p < 0.05).

^5^Significantly different from adults without disabilities (p < 0.05).

^6^Significantly different from adults living with others (p < 0.05).

NOTES: Categories shown for non-Hispanic adults are for those who selected only one racial group. Adults categorized as Hispanic may be of any race or combination of races. Other and multiple races non-Hispanic includes those who did not identify as American Indian and Alaska Native, Asian, Black, White, or Hispanic, and those who identified as more than one race. Data are based on a yes response to the survey question, “Do you take prescription medication for depression?” Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2023.

Figure 2 is a bar chart showing the percentage of adults age 18 and older who took medication for depression by race and Hispanic origin, disability status, and living arrangement in the United States in 2023.

Data table for Figure 2 Percentage of adults age 18 and older who took medication for depression, by race and Hispanic origin, disability status, and living arrangement: United States, 2023

Selected characteristic | Percent (95% confidence interval) | Standard error
Race and Hispanic origin
American Indian and Alaska Native, non-Hispanic | 6.9 (3.7–11.4) | 1.8
Asian, non-Hispanic | 3.4 (2.5–4.5) | 0.5
Black, non-Hispanic | 7.7 (6.6–8.9) | 0.6
White, non-Hispanic | 14.3 (13.6–14.9) | 0.3
Other and multiple races, non-Hispanic | 14.2 (10.4–18.8) | 2.0
Hispanic | 6.7 (5.8–7.6) | 0.4
Disability status
With disabilities | 28.2 (26.3–30.2) | 1.0
Without disabilities | 9.7 (9.3–10.2) | 0.2
Living arrangement
Living alone | 14.4 (13.7–15.2) | 0.4
Living with others | 10.9 (10.4–11.4) | 0.3

NOTES: Categories shown for non-Hispanic adults are for those who selected only one racial group. Adults categorized as Hispanic may be of any race or combination of races. Other and multiple races non-Hispanic includes those who did not identify as American Indian and Alaska Native, Asian, Black, White, or Hispanic, and those who identified as more than one race. Data are based on a yes response to the survey question, “Do you take prescription medication for depression?” Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2023.

## Were there differences in the percentage of adults who took medication for depression by family income?

- The percentage of adults who took prescription medication for depression decreased with increasing income as a percentage of the federal poverty level (FPL), ranging from 14.8% among those with incomes less than 100% FPL to 10.1% among those with incomes at or more than 400% FPL (Figure 3, Table 3).
- The percentage of adults who took medication for depression increased from 9.2% among those with less than high school to 13.2% among those with an associate’s degree or some college, and then declined to 10.9% among those with a bachelor’s degree or higher.

Figure 3 Percentage of adults age 18 and older who took medication for depression, by family income and education: United States, 2023

^1^Significant linear trend by family income (p < 0.05).

^2^Significant quadratic trend by education (p < 0.05).

NOTES: Family income is expressed as a percentage of the federal poverty level (FPL), which was calculated from the family’s income in the previous calendar year and family size using the U.S. Census Bureau’s poverty thresholds. Data are based on a yes response to the survey question, “Do you take prescription medication for depression?” Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2023.

Figure 3 is a bar chart showing the percentage of adults age 18 and older who took medication for depression by family income and education in the United States in 2023.

Data table for Figure 3 Percentage of adults age 18 and older who took medication for depression, by family income and education: United States, 2023

Selected characteristic | Percent (95% confidence interval) | Standard error
Family income
Less than 100% FPL | 14.8 (13.3–16.3) | 0.8
100% to less than 200% FPL | 13.2 (12.0–14.4) | 0.6
200% to less than 400% FPL | 11.2 (10.4–12.0) | 0.4
400% FPL or more | 10.1 (9.4–10.8) | 0.3
Education
Less than high school diploma or GED | 9.2 (7.9–10.6) | 0.7
High schoool diploma or GED | 11.0 (10.2–11.9) | 0.4
Associate’s degree or some college | 13.2 (12.3–14.1) | 0.5
Bachelor’s degree or higher | 10.9 (10.2–11.6) | 0.3

NOTES: Family income is expressed as a percentage of the federal poverty level (FPL), which was calculated from the family’s income in the previous calendar year and family size using the U.S. Census Bureau’s poverty thresholds. Data are based on a yes response to the survey question, “Do you take prescription medication for depression?” Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2023.

## Did the percentage of adults who took medication for depression vary by region or urbanization level?

- Adults living in the Midwest were more likely to take prescription medication for depression (14.2%) than those living in the Northeast (11.2%), South (11.0%), or West (9.9%). All other observed differences by region were not significant (Figure 4, Table 4).
- The percentage of adults who took medication for depression was higher among those living in nonmetropolitan areas (13.5%) and medium and small metropolitan areas (13.1%) compared with those living in large fringe metropolitan areas (10.7%) and large central metropolitan areas (9.5%).

Figure 4 Percentage of adults age 18 and older who took medication for depression, by region and urbanization level: United States, 2023

^1^Significantly different from Northeast, South, and West (p < 0.05).

^2^Significant linear trend (p < 0.05).

NOTES: Data are based on a yes response to the survey question, “Do you take prescription medication for depression?” Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2023.

Figure 4 is a bar chart showing the percentage of adults age 18 and older who took medication for depression by region and urbanization level in the United States in 2023.

Data table for Figure 4 Percentage of adults age 18 and older who took medication for depression, by region and urbanization level: United States, 2023

Selected characteristic | Percent (95% confidence interval) | Standard error
Region
Midwest | 14.2 (13.3–15.2) | 0.5
Northeast | 11.2 (10.1–12.4) | 0.6
South | 11.0 (10.2–11.8) | 0.4
West | 9.9 (9.1–10.8) | 0.4
Urbanization level
Large central metropolitan | 9.5 (8.8–10.2) | 0.4
Large fringe metropolitan | 10.7 (9.8–11.6) | 0.5
Medium and small metropolitan | 13.1 (12.2–14.0) | 0.5
Nonmetroplitan | 13.5 (12.3–14.9) | 0.7

NOTES: Data are based on a yes response to the survey question, “Do you take prescription medication for depression?” Estimates are based on household interviews of a sample of the U.S. civilian noninstitutionalized population.

SOURCE: National Center for Health Statistics, National Health Interview Survey, 2023.

## Summary

Using nationally representative data, this report describes the overall percentages of adults age 18 and older who took prescription medication for depression and measures disparities among adults by selected sociodemographic characteristics. In 2023, 11.4% of adults took medication for depression, with women being more than twice as likely as men to take medication for depression. White adults and adults who are other and multiple races were more likely than adults of all other racial and ethnic groups to take medication for depression. Adults with disabilities were nearly three times as likely to take medication for depression as those without disabilities. Adults living alone were more likely to take medication for depression than those living with others. The percentage of adults taking medication for depression decreased with increasing family income. The percentage of adults who took medication for depression was highest among those living in the Midwest and increased with decreasing urbanization.

## Definitions

[underlined: Disability status]: Categorized by the level of difficulty reported in the Washington Group Short Set on Functioning (3). The six domains of functioning include: seeing (even if wearing glasses), hearing (even if wearing hearing aids), mobility (walking or climbing stairs), communication (understanding or being understood by others), cognition (remembering or concentrating), and self-care (such as washing all over or dressing). Adults who respond “a lot of difficulty” or “cannot do at all or unable to do” to at least one domain are considered to have disabilities.

[underlined: Family income]: Based on FPL, which was calculated from the family’s income in the previous calendar year and family size using the U.S. Census Bureau’s poverty thresholds (4). Family income was imputed when missing (5).

[underlined: Living alone]: Living arrangements were defined by the number of adults and the number of children younger than age 18 living in the household. An adult was defined as living alone if one adult and no children younger than age 18 lived in the household. All other responses were categorized as living with others. Two categories were recoded: living alone and living with others.

[underlined: Race and Hispanic origin]: Categories shown for non-Hispanic adults are for those who selected only one racial group. Adults categorized as Hispanic may be of any race or combination of races. The category other and multiple races non-Hispanic includes those who did not identify as American Indian and Alaska Native, Asian, Black, White, or Hispanic, and those who identified as more than one race.

[underlined: Region]: Corresponds to the U.S. Census Bureau regions, defined as:

- Northeast: Connecticut, Maine, Massachusetts, New Hampshire, New Jersey, New York, Pennsylvania, Rhode Island, and Vermont
- Midwest: Illinois, Indiana, Iowa, Kansas, Michigan, Minnesota, Missouri, Nebraska, North Dakota, Ohio, South Dakota, and Wisconsin
- South: Alabama, Arkansas, Delaware, District of Columbia, Florida, Georgia, Kentucky, Louisiana, Maryland, Mississippi, North Carolina, Oklahoma, South Carolina, Tennessee, Texas, Virginia, and West Virginia
- West: Alaska, Arizona, California, Colorado, Hawaii, Idaho, Montana, New Mexico, Nevada, Oregon, Utah, Washington, and Wyoming.

[underlined: Urbanization level]: Metropolitan status and size were determined using the 2013 National Center for Health Statistics Urban–Rural Classification Scheme for counties (6). Large metropolitan areas are metropolitan statistical areas of 1 million or more people and are categorized into central and fringe counties. Medium and small metropolitan areas are counties in metropolitan statistical areas of 250,000–999,999 people and less than 250,000 people, respectively. Nonmetropolitan areas are counties in micropolitan statistical areas and noncore counties.

## Data source and methods

Data from the 2023 NHIS were used for this analysis. NHIS is a nationally representative household survey of the U.S. civilian noninstitutionalized population. It is conducted continuously throughout the year by the National Center for Health Statistics (NCHS). Interviews are typically initiated face-to-face in respondents’ homes with follow-ups conducted over the telephone as needed (7). For more information about NHIS, visit https://www.cdc.gov/nchs/nhis.htm.

Point estimates and corresponding variances for this analysis were calculated using SAS-callable SUDAAN software (8) to account for the complex sample design of NHIS. All estimates are based on self-report and meet NCHS data presentation standards for proportions (9). Differences between percentages were evaluated using two-sided significance tests at the 0.05 level. Linear and quadratic trends by age group and family income were evaluated using orthogonal polynomials in logistic regression.

## About the authors

Nazik Elgaddal, Julie D. Weeks, and Laryssa Mykyta are with the National Center for Health Statistics, Division of Analysis and Epidemiology.

## References

1 National Institute of Mental Health. Depression. 2024. Available from: https://www.nimh.nih.gov/health/topics/depression.
2 McCarron RM, Shapiro B, Rawles J, Luo J. Depression. Ann Intern Med. 2021 May;174(5):ITC65–ITC80. DOI: 10.7326/AITC202105180.33971098
3 Washington Group on Disability Statistics. WG Short Set on Functioning (WG-SS). 2022. Available from: https://www.washingtongroup-disability.com/question-sets/wg-short-set-on-functioning-wg-ss/.
4 U.S. Census Bureau. Poverty thresholds. 2023. Available from: https://www.census.gov/data/tables/time-series/demo/income-poverty/historical-poverty-thresholds.html.
5 National Center for Health Statistics. Multiple imputation of family income in 2023 National Health Interview Survey: Methods. 2024. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/NHIS/2023/NHIS2023-imputation-techdoc-508.pdf.
6 Ingram DD, Franco SJ. 2013 NCHS urban−rural classification scheme for counties. Vital Health Stat 2(166). 2014.
7 National Center for Health Statistics. National Health Interview Survey, 2023 survey description. 2024. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/NHIS/2023/srvydesc-508.pdf.
8 RTI International. SUDAAN (Release 11.0.3) [computer software]. 2018. Available from: https://www.rti.org/impact/sudaanr-statistical-software-analyzing-correlated-data.
9 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. Vital Health Stat 2(175). 2017.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Analysis and Epidemiology

Irma E. Arispe, Ph.D., Director

Kimberly A. Lochner, Sc.D., Associate Director for Science

For more NCHS Data Briefs, visit:https://www.cdc.gov/nchs/products/databriefs.htm.

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/.

For questions or general information about NCHS: Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info