# No. 516 Prevalence of Total, Diagnosed, and Undiagnosed Diabetes in Adults: United States, August 2021–August 2023

### Introduction

This report presents the prevalence of diagnosed, undiagnosed, and total diabetes in U.S. adults during August 2021–August 2023. Trends in diagnosed, undiagnosed, and total diabetes prevalence in adults from 1999–2000 through August 2021–August 2023 are also shown.

### Methods

Prevalence of self-reported diagnosed, undiagnosed, and total diabetes was estimated using August 2021–August 2023 National Health and Nutrition Examination Survey data. Diagnosed diabetes was defined as answering “yes” to the question: “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Undiagnosed diabetes was defined as reporting never receiving a diabetes diagnosis from a healthcare provider and 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5%. Total diabetes was the combined prevalence of diagnosed and undiagnosed diabetes. Standard errors of percentages were estimated using Taylor series linearization. Pairwise differences between groups were evaluated using t statistics, and stated differences were statistically significant at p less than 0.05. Orthogonal contrasts were used to test for linear trends except for trends over time, where a linear regression model was used accounting for the unequal time between survey cycles.

### Key findings

During August 2021–August 2023, the prevalence of total, diagnosed, and undiagnosed diabetes in U.S. adults was 15.8%, 11.3%, and 4.5%, respectively. The prevalence of total and diagnosed diabetes was higher in men than among women and decreased with increasing educational attainment. The prevalence of total, diagnosed, and undiagnosed diabetes increased with increasing age and increasing weight status. The age-adjusted prevalence of total and diagnosed diabetes increased from 9.7% to 14.3% and from 5.9% to 10.1%, respectively, between 1999–2000 and August 2021–August 2023.No change was seen between 2017–March 2020 and August 2021–August 2023.

Key findings

Data from the National Health and Nutrition Examination Survey

- During August 2021–August 2023, the prevalence of total diabetes was 15.8%, diagnosed diabetes was 11.3%, and undiagnosed diabetes was 4.5% in U.S. adults.
- Total and diagnosed diabetes prevalence was higher in men (18.0% and 12.9%, respectively) than in women (13.7% and 9.7%, respectively).
- Total, diagnosed, and undiagnosed diabetes prevalence increased with age.
- Total, diagnosed, and undiagnosed diabetes prevalence increased with increasing weight status.
- Total and diagnosed diabetes prevalence decreased with increasing educational attainment.
- The age-adjusted prevalence of total and diagnosed diabetes increased between 1999–2000 and August 2021–August 2023.

Diabetes mellitus is a chronic disease and metabolic disorder resulting in elevated blood glucose levels. It is categorized as type 1 or type 2 diabetes, gestational diabetes, and other specific types due to other causes (1). Uncontrolled blood glucose levels over a long period of time can affect multiple organ systems, including the nervous system, kidneys, eyes, heart, and blood vessels (2). Diabetes is a major cause of morbidity and mortality in the United States (3). This report presents the prevalence of diagnosed, undiagnosed, and total diabetes (excluding gestational diabetes) in U.S. adults during August 2021–August 2023.

## During August 2021–August 2023, the prevalence of total and diagnosed diabetes was higher in men than in women.

- The prevalence of total diabetes was 15.8% in all adults. The prevalence of diagnosed and undiagnosed diabetes was 11.3% and 4.5%, respectively (Figure 1, Table 1).
- Men had a higher prevalence of total and diagnosed diabetes (18.0% and 12.9%, respectively) compared with women (13.7% and 9.7%).
- The observed difference in undiagnosed diabetes between men and women was not significant.

Figure 1 Prevalence of total, diagnosed, and undiagnosed diabetes in adults age 20 and older, by sex: United States, August 2021–August 2023

^1^ Significantly different from women (p < 0.05).

NOTES: Diagnosed and undiagnosed diabetes may not sum to total due to rounding. Estimates for diagnosed diabetes are based on responses to the survey question, “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Estimates for undiagnosed diabetes are based on an 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5% in a participant who reported never receiving a diabetes diagnosis from a healthcare provider. Age-adjusted estimates for adults age 20 and older are total diabetes: 14.3% all, 16.6% men, and 12.2% women; diagnosed diabetes: 10.1% all, 11.7% men, and 8.6% women; and undiagnosed diabetes: 4.2% all, 4.9% men, and 3.5% women, age adjusted by the direct method to the U.S. Census 2000 population using age groups 20–39, 40–59, and 60 and older.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

Figure 1 is a bar chart on total, diagnosed, and undiagnosed diabetes prevalence in adults age 20 and older by sex from August 2021 through August 2023.

Data table for Figure 1 Prevalence of total, diagnosed, and undiagnosed diabetes in adults age 20 and older, by sex: United States, August 2021–August 2023

Diabetes category and sex | Sample size | Percent (95% confidence interval) | Standard error | Age adjusted
Diabetes category and sex | Sample size | Percent (95% confidence interval) | Standard error | Percent (95% confidence interval) | Standard error
Total | 2,938 | 15.8 (13.6–18.2) | 1.1 | 14.3 (12.1–16.7) | 1.0
Men | 1,306 | 18.0 (15.7–20.4) | 1.1 | 16.6 (14.0–19.4) | 1.2
Women | 1,632 | 13.7 (11.0–16.7) | 1.3 | 12.2 (9.9–14.8) | 1.1
Diagnosed | 2,938 | 11.3 (9.3–13.5) | 1.0 | 10.1 (8.3–12.1) | 0.8
Men | 1,306 | 12.9 (11.0–15.0) | 0.9 | 11.7 (9.9–13.7) | 0.8
Women | 1,632 | 9.7 (7.3–12.7) | 1.2 | 8.6 (6.7–10.9) | 0.9
Undiagnosed | 2,938 | 4.5 (3.3–5.9) | 0.6 | 4.2 (2.9–5.7) | 0.6
Men | 1,306 | 5.1 (3.6–6.9) | 0.8 | 4.9 (3.3–6.9) | 0.8
Women | 1,632 | 3.9 (2.8–5.3) | 0.6 | 3.5 (2.4–5.1) | 0.6

NOTES: Sample size is unweighted. Estimates are weighted using fasting sample weights. Estimates for diagnosed diabetes are based on responses to the survey question, “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Estimates for undiagnosed diabetes are based on an 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5% in a participant who reported never receiving a diabetes diagnosis from a healthcare provider. Age-adjusted estimates for adults age 20 and older were age adjusted by the direct method to the U.S. Census 2000 population using age groups 20–39, 40–59, and 60 and older.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

## The prevalence of total, diagnosed, and undiagnosed diabetes increased with age.

- The prevalence of total diabetes increased from 3.6% in adults ages 20–39 to 17.7% for ages 40–59 and 27.3% for age 60 and older (Figure 2, Table 2).
- The prevalence of diagnosed diabetes increased from 2.2% in adults ages 20–39 to 12.1% for ages 40–59 and 20.5% for age 60 and older.
- The prevalence of undiagnosed diabetes increased from 1.3% in adults ages 20–39 to 5.6% for ages 40–59 and 6.8% for age 60 and older.

Figure 2 Prevalence of total, diagnosed, and undiagnosed diabetes in adults age 20 and older, by age group: United States, August 2021–August 2023

^1^ Significant increasing linear trend for total, diagnosed, and undiagnosed diabetes (p < 0.05).

NOTES: Diagnosed and undiagnosed diabetes may not sum to total due to rounding. Estimates for diagnosed diabetes are based on responses to the survey question, “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Estimates for undiagnosed diabetes are based on an 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5% in a participant who reported never receiving a diabetes diagnosis from a healthcare provider.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

Figure 2 is a bar chart on total, diagnosed, and undiagnosed diabetes prevalence in adults by age group during August 2021 through August 2023.

Data table for Figure 2 Prevalence of total, diagnosed, and undiagnosed diabetes in adults age 20 and older, by age group: United States, August 2021–August 2023

Diabetes category and age group | Sample size | Percent (95% confidence interval) | Standard error
Total
20–39 | 688 | 3.6 (2.0–5.9) | 0.9
40–59 | 861 | 17.7 (14.7–21.0) | 1.4
60 and older | 1,389 | 27.3 (23.0–31.9) | 2.0
Diagnosed
20–39 | 688 | 2.2 (1.1–4.0) | 0.6
40–59 | 861 | 12.1 (10.0–14.5) | 1.0
60 and older | 1,389 | 20.5 (16.2–25.3) | 2.1
Undiagnosed
20–39 | 688 | 1.3 (0.5–3.0) | 0.5
40–59 | 861 | 5.6 (3.3–8.9) | 1.2
60 and older | 1,389 | 6.8 (5.3–8.5) | 0.7

NOTES: Sample size is unweighted. Estimates are weighted using fasting sample weights. Estimates for diagnosed diabetes are based on responses to the survey question, “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Estimates for undiagnosed diabetes are based on an 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5% in a participant who reported never receiving a diabetes diagnosis from a healthcare provider.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

## The prevalence of total, diagnosed, and undiagnosed diabetes increased with increasing weight status.

- The prevalence of total diabetes increased from 6.8% in adults in the underweight or normal weight category to 12.3% in those in the overweight category and 24.2% in adults with obesity (Figure 3, Table 3).
- The prevalence of diagnosed diabetes increased from 5.2% in adults in the underweight or normal weight category to 9.5% in those in the overweight category and 16.3% in adults with obesity.
- The prevalence of undiagnosed diabetes increased from 1.6% in adults in the underweight or normal weight category to 2.8% in those in the overweight category and 7.9% in adults with obesity.

Figure 3 Prevalence of total, diagnosed, and undiagnosed diabetes in adults age 20 and older, by weight status: United States, August 2021–August 2023

^1^ Significant increasing linear trend for total, diagnosed, and undiagnosed diabetes (p < 0.05).

NOTES: Estimates for diagnosed diabetes are based on responses to the survey question, “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Estimates for undiagnosed diabetes are based on an 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5% in a participant who reported never receiving a diabetes diagnosis from a healthcare provider. Body mass index is weight in kilograms divided by height in meters squared. Weight status categories are defined as underweight or normal weight, body mass index less than 25.0; overweight, body mass index 25.0–29.9; and obesity, body mass index 30.0 or more.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

Figure 3 is a bar chart on total, diagnosed, and undiagnosed diabetes prevalence in adults by weight status during August 2021 through August 2023.

Data table for Figure 3 Prevalence of total, diagnosed, and undiagnosed diabetes in adults age 20 and older, by weight status: United States, August 2021–August 2023

Diabetes category and weight status | Sample size | Percent (95% confidence interval) | Standard error
Total
Underweight or normal weight | 779 | 6.8 (5.1– 8.9) | 0.9
Overweight | 936 | 12.3 (9.6–15.5) | 1.3
Obesity | 1,190 | 24.2 (21.1–27.5) | 1.5
Diagnosed
Underweight or normal weight | 779 | 5.2 (3.1–8.2) | 1.1
Overweight | 936 | 9.5 (7.1–12.5) | 1.2
Obesity | 1,190 | 16.3 (13.8–19.1) | 1.2
Undiagnosed
Underweight or normal weight | 779 | 1.6 (0.6–3.4) | 0.6
Overweight | 936 | 2.8 (1.8–4.1) | 0.4
Obesity | 1,190 | 7.9 (5.5–10.9) | 1.2

NOTES: Sample size is unweighted. Estimates are weighted using fasting sample weights. Estimates for diagnosed diabetes are based on responses to the survey question, “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Estimates for undiagnosed diabetes are based on an 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5% in a participant who reported never receiving a diabetes diagnosis from a healthcare provider. Body mass index is weight in kilograms divided by height in meters squared. Weight status categories are defined as underweight or normal weight, body mass index less than 25.0; overweight, body mass index 25.0–29.9; and obesity, body mass index 30.0 or more.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

## The prevalence of total and diagnosed diabetes decreased with increasing levels of educational attainment.

- The prevalence of total diabetes decreased from 19.6% in adults with a high school degree, GED, or less to 17.2% in those with some college education and 10.7% in adults with a bachelor’s degree or more (Figure 4, Table 4).
- The prevalence of diagnosed diabetes decreased from 14.6% in adults with a high school degree, GED, or less to 12.0% in those with some college education and 7.3% in adults with a bachelor’s degree or more.
- No significant differences were seen by educational attainment for those with undiagnosed diabetes.

Figure 4 Prevalence of total, diagnosed, and undiagnosed diabetes in adults age 20 and older, by educational attainment: United States, August 2021–August 2023

^1^ Significant decreasing linear trend (p < 0.05).

NOTES: Estimates are weighted using fasting sample weights. Estimates for diagnosed diabetes are based on responses to the survey question, “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Estimates for undiagnosed diabetes are based on an 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5% in a participant who reported never receiving a diabetes diagnosis from a healthcare provider.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

Figure 4 is a bar chart on total, diagnosed, and undiagnosed diabetes prevalence in adults by educational attainment during August 2021 through August 2023.

Data table for Figure 4 Prevalence of total, diagnosed, and undiagnosed diabetes in adults age 20 and older, by educational attainment: United States, August 2021–August 2023

Diabetes category and education level | Sample size | Percent (95% confidence interval) | Standard error
Total
High school degree, GED, or less | 932 | 19.6 (15.8–24.0) | 1.9
Some college | 884 | 17.2 (14.1–20.7) | 1.5
Bachelor’s degree or more | 1,122 | 10.7 (7.8–14.2) | 1.4
Diagnosed
High school degree, GED, or less | 932 | 14.6 (11.5–18.3) | 1.5
Some college | 884 | 12.0 (9.4–14.9) | 1.3
Bachelor’s degree or more | 1,122 | 7.3 (4.8–10.6) | 1.3
Undiagnosed
High school degree, GED, or less | 932 | 5.0 (3.5–6.9) | 0.8
Some college | 884 | 5.2 (3.3–7.9) | 1.0
Bachelor’s degree or more | 1,122 | 3.4 (1.9–5.4) | 0.8

NOTES: Sample size is unweighted. Estimates are weighted using fasting sample weights. Estimates for diagnosed diabetes are based on responses to the survey question, “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Estimates for undiagnosed diabetes are based on an 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5% in a participant who reported never receiving a diabetes diagnosis from a healthcare provider.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, August 2021–August 2023.

## The age-adjusted prevalence of total and diagnosed diabetes increased between 1999–2000 and August 2021–August 2023.

- The age-adjusted prevalence of total diabetes increased from 9.7% in 1999–2000 to 14.3% in August 2021–August 2023 (Figure 5, Table 5).
- The age-adjusted prevalence of diagnosed diabetes increased from 5.9% in 1999–2000 to 10.1% in August 2021–August 2023.
- From 1999–2000 through August 2021–August 2023, the age-adjusted prevalence of undiagnosed diabetes did not change significantly.
- Between 2017–March 2020 and August 2021–August 2023, no significant differences were seen in age-adjusted prevalence of total (14.8% to 14.3%), diagnosed (10.6% to 10.1%), and undiagnosed (4.2% each) diabetes.

Figure 5 Trends in age-adjusted prevalence of total, diagnosed, and undiagnosed diabetes in adults age 20 and older: United States, 1999–2000 through August 2021–August 2023

^1^ Significant increasing linear trend (p < 0.05).

NOTES: Fasting glucose values were adjusted using forward regression equations provided by the National Center for Health Statistics. Estimates for diagnosed diabetes are based on responses to the survey question, “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Estimates for undiagnosed diabetes are based on an 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5% in a participant who reported never receiving a diabetes diagnosis from a healthcare provider. Estimates are age adjusted by the direct method to the U.S. Census 2000 population using the age groups 20–39, 40–59, and 60 and older.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Surveys, 1999–2000 through August 2021–August 2023.

Figure 5 is a line graph on trends in age-adjusted prevalence of total, diagnosed, and undiagnosed diabetes between 1999 through 2000 and August 2021 through August 2023.

Data table for Figure 5 Trends in age-adjusted prevalence of total, diagnosed, and undiagnosed diabetes in adults age 20 and older: United States, 1999–2000 through August 2021–August 2023

Survey year | Sample size | Total diabetes (95% confidence interval) | Standard error | Diagnosed diabetes (95% confidence interval) | Standard error | Undiagnosed diabetes (95% confidence interval) | Standard error
1999–2000 | 1,739 | 9.7 (7.6–12.1) | 1.0 | 5.9 (4.1–8.0) | 0.9 | 3.8 (2.7–5.1) | 0.5
2001–2002 | 2,078 | 11.5 (9.3–13.9) | 1.0 | 6.8 (5.3–8.6) | 0.7 | 4.7 (3.8–5.7) | 0.4
2003–2004 | 1,874 | 11.2 (9.2–13.4) | 0.9 | 7.2 (5.6–9.0) | 0.7 | 4.0 (2.7–5.7) | 0.7
2005–2006 | 1,824 | 11.6 (9.7–13.8) | 0.9 | 7.7 (6.3–9.3) | 0.7 | 3.9 (2.7–5.4) | 0.6
2007–2008 | 2,329 | 12.7 (10.8–14.8) | 0.9 | 8.3 (6.8–10.0) | 0.7 | 4.4 (3.5–5.4) | 0.4
2009–2010 | 2,585 | 12.6 (10.5–14.9) | 0.9 | 8.1 (6.4–10.0) | 0.7 | 4.5 (3.6–5.6) | 0.4
2011–2012 | 2,287 | 12.5 (9.9–15.5) | 1.2 | 8.5 (6.4–11.0) | 1.0 | 4.0 (2.8–5.4) | 0.6
2013–2014 | 2,368 | 13.0 (11.3–15.0) | 0.8 | 9.3 (7.8–11.0) | 0.7 | 3.7 (3.0–4.6) | 0.4
2015–2016 | 2,244 | 14.9 (12.7–17.3) | 1.0 | 10.0 (8.4–11.9) | 0.8 | 4.8 (3.4–6.6) | 0.7
2017–2020 | 3,757 | 14.8 (13.1–16.7) | 0.8 | 10.6 (9.1–12.2) | 0.7 | 4.2 (3.6–4.9) | 0.3
August 2021–August 2023 | 2,938 | 14.3 (12.1–16.7) | 1.0 | 10.1 (8.3–12.1) | 0.8 | 4.2 (2.9–5.7) | 0.6

NOTES: Sample size is unweighted. Estimates are weighted using fasting sample weights. Fasting glucose values were adjusted using forward regression equations provided by the National Center for Health Statistics. Estimates for diagnosed diabetes are based on responses to the survey question, “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?” Estimates for undiagnosed diabetes are based on an 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5% in a participant who reported never receiving a diabetes diagnosis from a healthcare provider. Estimates are age adjusted by the direct method to the U.S. Census 2000 population using the age groups 20–39, 40–59, and 60 and older.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Surveys, 1999–2000 through August 2021–August 2023.

## Summary

During August 2021–August 2023, the prevalence of total diabetes was 15.8%, diagnosed diabetes was 11.3%, and undiagnosed diabetes was 4.5%. Consequently, slightly more than one-quarter of adults with diabetes had undiagnosed diabetes. Men had a higher prevalence of total and diagnosed diabetes than women. Total, diagnosed, and undiagnosed diabetes prevalence increased with age and increasing weight status. The prevalence of total and diagnosed diabetes decreased with increasing educational attainment. The age-adjusted prevalence of total and diagnosed diabetes increased over time, from 1999–2000 through August 2021–August 2023. Continued monitoring of both diagnosed and undiagnosed diabetes will provide essential information about the prevalence of diabetes in adults in the United States.

## Definitions

[underlined: Diagnosed diabetes]: Defined as the survey respondent answering yes to the question: “Other than during pregnancy, have you ever been told by a doctor or health professional that you have diabetes or sugar diabetes?”

[underlined: Undiagnosed diabetes]: Defined as the survey respondent reporting never having received a diabetes diagnosis from a healthcare provider and 8- to 24-hour fasting plasma glucose greater than or equal to 126 mg/dL or hemoglobin A1c greater than or equal to 6.5%.

[underlined: Total diabetes]: Combined prevalence of diagnosed and undiagnosed diabetes.

[underlined: Weight status]: Body mass index is calculated as weight in kilograms divided by height in meters squared. Normal or underweight is defined as a body mass index less than 25. Overweight is defined as a body mass index greater than or equal to 25 but less than 30. Obesity is defined as a body mass index greater than or equal to 30.

## Data source and methods

Data from the August 2021–August 2023 National Health and Nutrition Examination Survey were used for analysis. The survey has a cross-sectional, complex, multistage probability sample design representative of the U.S. civilian noninstitutionalized population. The survey consists of interviews conducted in participants’ homes. Standardized health examinations and laboratory tests on blood and other specimens were conducted in mobile examination centers. However, due to the COVID-19 pandemic, survey operations were altered. Details of these changes in program and collection procedures can be found in the “Plan and Operations of the National Health and Nutrition Examination Survey, August 2021–August 2023” (4).

Criteria from the American Diabetes Association were used to define diabetes (1). Fasting plasma glucose data after an 8- to 24-hour fast were used. Fasting sample weights were used to account for differential probabilities of selection, nonresponse, and noncoverage. Analyses excluded pregnant women.

Standard errors of percentages were estimated using Taylor series linearization. Pairwise differences between groups were evaluated using t statistics. Stated differences were statistically significant at p less than 0.05. Orthogonal contrasts were used to test for linear trends across categories of age, educational attainment, and weight status. Linear regression models were used to evaluate linear and quadratic trends across survey timepoints from 1999–2000 through August 2021–August 2023 (adjusting for differential time between survey cycles) and adjusted for age. Fasting plasma glucose values were adjusted using forward regression equations provided by the National Center for Health Statistics (5–7). Statistical analyses were conducted using SAS release 9.4 (SAS Institute Inc., Cary, N.C.) and SAS-callable SUDAAN release 11.0 (RTI International, Research Triangle Park, N.C.).

## About the authors

Jane A. Gwira was a Centers for Disease Control and Prevention Preventive Medicine resident at the National Center for Health Statistics, Division of Health and Nutrition Examination Surveys, during the analysis and writing of this report. Cheryl D. Fryar and Qiuping Gu are with the National Center for Health Statistics, Division of Health and Nutrition Examination Surveys.

## References

1. American Diabetes Association. Diagnosis and classification of diabetes: Standards of care in diabetes—2024. Diabetes Care 47(Supp1):S20–S42. 2024.38078589
2. Beagley J, Guariguata L, Weil C, Motala AA. Global estimates of undiagnosed diabetes in adults. Diabetes Res Clin Pract 103(2):150–60. 2014.24300018
3. Heron M. Deaths: Leading causes for 2016. National Vital Statistics Reports; vol 67 no 6. Hyattsville, MD: National Center for Health Statistics. 2018.
4. Terry AL, Chiappa MM, McAllister J, Woodwell DA, Graber JE. Plan and operations of the National Health and Nutrition Examination Survey, August 2021–August 2023. National Center for Health Statistics. Vital Health Stat 1(66). 2024. DOI: 10.15620/cdc/151927.
5. National Center for Health Statistics. National Health and Nutrition Examination Survey: 2005–2006 data documentation, codebook, and frequencies—plasma fasting glucose & insulin (GLU_D). 2008. Available from: https://wwwn.cdc.gov/Nchs/Nhanes/2005-2006/GLU_D.htm.
6. National Center for Health Statistics. National Health and Nutrition Examination Survey: 2007–2008 data documentation, codebook, and frequencies, plasma fasting glucose & insulin (GLU_E). 2010. Available from: https://wwwn.cdc.gov/Nchs/Nhanes/2007-2008/GLU_E.htm.
7. National Center for Health Statistics. National Health and Nutrition Examination Survey: 2015–2016 data documentation, codebook, and frequencies, plasma fasting glucose (GLU_I). 2018. Available from: https://wwwn.cdc.gov/Nchs/Nhanes/2015-2016/GLU_I.htm.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Health and Nutrition Examination Surveys

Alan E. Simon, M.D., Director

Lara J. Akinbami, M.D., Associate Director for Science

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/.

For questions or general information about NCHS:

Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info

ISSN 1941–4927 Print ed.

ISSN 1941–4935 Online ed.