# No. 503 Emergency Department Visit Rates by Selected Characteristics: United States, 2022

### Introduction

This report presents characteristics of emergency department (ED) visits by age group, sex, race and ethnicity, payment source, and mention of COVID-19, using data from the 2022 National Hospital Ambulatory Medical Care Survey (NHAMCS).

### Methods

Data for this report are from NHAMCS, an annual, nationally representative survey of nonfederal, general, and short-stay hospitals. Data analyses were performed using the statistical packages SAS version 9.4 and SAS-callable SUDAAN. Two-tailed t tests with a significance level of p < 0.05 were used to determine statistically significant differences between ED visit rates.

### Key findings

The overall ED visit rate was 47 visits per 100 people in 2022, and the ED visit rates were highest for infants younger than age 1 year (99 visits per 100 infants) and adults ages 75 and older (76 per 100 adults). The ED visit rate for Black or African American non-Hispanic people (91) was the highest among the selected racial and ethnic groups. In 2022, a COVID-19 diagnosis was confirmed for 4.8% of all ED patient visits.

Key findings

### Data from the National Hospital Ambulatory Medical Care Survey

- The overall emergency department (ED) visit rate was 47 visits per 100 people in 2022.
- ED visit rates were highest for infants younger than age 1 year (99 visits per 100 infants) and adults ages 75 and older (76 per 100 people).
- The ED visit rate for Black or African-American non-Hispanic people (91) was the highest among the selected racial and ethnic groups.
- The ED visit rate for patients with private insurance was lowest compared with all other primary expected sources of payment that were considered; the rate for patients with Medicaid, Children’s Health Insurance Program (CHIP), or other state-based programs was highest.
- In 2022, a COVID-19 diagnosis was confirmed for 4.8% of all ED patient visits.

In 2022, 155 million emergency department (ED) visits occurred in the United States (1). During that year, about 5% of children had two or more ED visits in the past 12 months, and about 20% of adults had visited the ED in the past 12 months (2, 3). This report presents characteristics of ED visits by age group, sex, race and ethnicity, payment source, and mention of COVID-19, using data from the 2022 National Hospital Ambulatory Medical Care Survey (NHAMCS) (4).

## What was the ED visit rate in 2022, and did visit rates vary by age?

- The total ED visit rate was 47 visits per 100 people in 2022 (Figure 1, Table 1).
- The ED visit rate was highest for infants younger than age 1 year (99 visits per 100 infants), followed by adults ages 75 and older (76 visits per 100 adults). These rates were higher than for all other age groups.
- ED visit rates were similar for patients in age groups between 1 and 74, ranging from 41 to 47 visits per 100 people.

Figure 1 Emergency department visit rate, by age group: United States, 2022

^1^Significantly different from ages younger than 1 year.

^2^Significantly different from ages 75 and older.

NOTES: Data are based on a sample of 16,025 emergency department visits by patients in 2022, representing about 155 million emergency department visits. Visit rates are based on the July 1, 2022, set of estimates of the U.S. civilian noninstitutionalized population, as developed by the U.S. Census Bureau’s Population Division.

SOURCE: National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2022.

Figure 1 is a bar chart showing emergency department visit rates per 100 people by the age groups younger than 1 year, 1-17 years, 18-44, 45-64, 65-74, and 75 and older for 2022.

Data table for Figure 1 Emergency department visit rate, by age group: United States, 2022

Age group (years) | Visit rate per 100 people | Standard error | 95% confidence interval
Total | 47 | 3.1 | 41.2–53.4
Younger than 1 | 99 | 12.7 | 73.5–124.3
1–17 | 41 | 4.2 | 32.5–49.3
18–44 | 47 | 3.7 | 39.2–54.0
45–64 | 44 | 3.1 | 37.6–49.9
65–74 | 46 | 3.7 | 39.0–53.7
75 and older | 76 | 7.0 | 62.0–90.0

NOTES: Data are based on a sample of 16,025 emergency department visits by patients in 2022, representing approximately 155 million emergency department visits. Visit rates are based on the July 1, 2022, set of estimates of the U.S. civilian noninstitutionalized population, as developed by the U.S. Census Bureau’s Population Division.

SOURCE: National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2022.

## Did ED visit rates vary by sex or race and ethnicity?

- The 2022 ED visit rate for females (51 visits per 100 females) was similar to the ED visit rate for males (44 visits per 100 males) (Figure 2, Table 2).
- In 2022, the ED visit rate was highest for Black or African-American non-Hispanic (subsequently, Black) people (91 visits per 100 people) compared with White non-Hispanic (subsequently, White) people (45), Hispanic people (41), and people of other non-Hispanic races (subsequently, other races) (21). Rates were lowest among other races.

Figure 2 Emergency department visit rate, by sex and race and ethnicity: United States, 2022

^1^Significantly different from other races non-Hispanic (subsequently, other races).

^2^Significantly different from Black or African American non-Hispanic.

NOTES: Data are based on a sample of 16,025 emergency department visits by patients in 2022, representing about 155 million emergency department visits.Visit rates are based on the July 1, 2022, sets of estimates of the U.S. civilian noninstitutionalized population, as developed by the U.S. Census Bureau’sPopulation Division. For 2022, 16.5% of weighted race data and 16.9% of weighted ethnicity data were missing for emergency department visits, and race andethnicity were imputed for these missing records. Race and Hispanic ethnicity were collected separately, imputed, and converted into a single combined variablethat includes Black or African American non-Hispanic, White non-Hispanic, other races, and Hispanic. Race and ethnicity data were imputed on the data file usinga model-based, single, sequential-regression imputation method. Missing race values were imputed to be Black or African American, Other, or White. Hispanicethnicity was imputed to be Hispanic or non-Hispanic. People of Hispanic origin may be of any race. Other races includes Asian, Native Hawaiian or Other PacificIslander, American Indian and Alaska Native, and two or more races.

SOURCE: National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2022.

Figure 2 is a bar chart showing emergency department visit rates per 100 people by sex and race and ethnicity for the categories Black or African American non-Hispanic, White non-Hispanic, other races non-Hispanic, and Hispanic for 2022.

Data table for Figure 2 Emergency department visit rate, by sex and race and ethnicity: United States, 2022

Characteristic | Visit rate per 100 people | Standard error | 95% confidence interval
Total | 47 | 3.1 | 41.2–53.4
Female | 51 | 3.5 | 43.9–58.0
Male | 44 | 2.8 | 37.9–49.1
Black or African American, non-Hispanic | 91 | 10.1 | 70.8–110.9
White, non-Hispanic | 45 | 3.5 | 37.6–51.4
Other races, non-Hispanic | 21 | 2.8 | 15.0–26.0
Hispanic | 41 | 4.6 | 31.8–49.8

NOTES: Data are based on a sample of 16,025 emergency department visits by patients in 2022, representing approximately 155 million emergency department visits. Visit rates are based on the July 1, 2022, sets of estimates of the U.S. civilian noninstitutionalized population, as developed by the U.S. Census Bureau’s Population Division. For 2022, 16.5% of weighted race data and 16.9% of weighted ethnicity data were missing for emergency department visits, and race and ethnicity were imputed for these missing records. Race and Hispanic ethnicity were collected separately, imputed, and converted into a single combined variable that includes Black or African American non-Hispanic, White non-Hispanic, other races non-Hispanic, and Hispanic. Race and ethnicity data were imputed on the data file using a model-based, single, sequential-regression imputation method. Missing race values were imputed to be Black or African American, Other, or White. Hispanic ethnicity was imputed to be Hispanic or non-Hispanic. People of Hispanic origin may be of any race. Other races non-Hispanic includes Asian, Native Hawaiian or Other Pacific Islander, American Indian and Alaska Native, and two or more races.

SOURCE: National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2022.

## What were the ED visit rates for each primary expected source of payment, and did these rates vary?

- The ED visit rate was highest for patients with Medicaid, Children’s Health Insurance Program (CHIP), or other state-based programs (99 visits per 100 people) and lowest for patients with private insurance (21) (Figure 3, Table 3).
- The ED visit rate for patients with Medicare (56) was higher than the rate for patients with no insurance (35). The observed difference in the ED visit rate between patients with Medicare and other payment sources (42) was not significant.

Figure 3 Emergency department visit rate, by primary expected source of payment:United States, 2022

^1^Significantly different from all other sources of payment.

^2^Significantly different from no insurance.

^3^Includes worker’s compensation and other sources of payment.

NOTES: Data are based on a sample of 16,025 emergency department visits by patients in 2022, representing about 155 million emergency department visits.Visit rates are based on a patient’s primary expected source of payment and proportional insurance data from the 2022 National Health Interview Survey (see: https://www.cdc.gov/nchs/nhis/2020nhis.htm).

SOURCE: National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2022.

Figure 3 is a bar chart showing emergency department visit rates per 100 people by primary expected source of payment for the categories Medicaid, Children’s Health Insurance Program, or other state-based programs; Medicare; other payment sources; no insurance; and private for 2022.

Data table for Figure 3 Emergency department visit rate, by primary expected source of payment: United States, 2022

Primary expected source of payment | Visit rate per 100 people | Standard error | 95% confidence interval
Medicaid, Children’s Health Insurance Program, or other state-based programs | 99 | 9.8 | 79.5–118.5
Medicare | 56 | 4.9 | 46.3–65.6
Other | 42 | 6.0 | 29.8–53.6
No insurance | 35 | 6.7 | 21.9–48.4
Private insurance | 21 | 1.5 | 18.1–24.0

NOTES: Data are based on a sample of 16,025 emergency department visits by patients in 2022, representing approximately 155 million emergency department visits. Visit rates are based on the patient’s primary expected source of payment and proportional insurance data from the 2022 National Health Interview Survey (see: https://www.cdc.gov/nchs/nhis/2020nhis.htm).

SOURCE: National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2022.

## What percentage of ED visits were related to COVID-19?

- An estimated 25.2% of all ED visits in 2022 had any mention of COVID-19, which included COVID-19 testing (Figure 4, Table 4).
- Cases of COVID-19 were confirmed at 4.8% of ED visits.
- The percentage of ED visits with a COVID-19 test or screening was 22.8%, and 2.8% of visits included other mentions of COVID-19.

Figure 4 Percentage of emergency department visits with mentions of COVID-19:United States, 2022

^1^Consists of all measures listed in this figure.

^2^Consists of International Classification of Diseases, 10th Revision, Clinical Modification (ICD–10–CM) code U07.1.

^3^Consists of ICD–10–CM code Z11.52, a visit involving a COVID-19 test or COVID-19 antibody test, and any mention of COVID-19 testing or screening invalidated verbatim item notes or medication fields.

^4^Consists of ICD–10–CM codes U09.9, Z20.822, Z86.16, and any other mention of COVID-19 in validated verbatim item notes or medication fields that did notmention testing or screening.

NOTES: Categories are not mutually exclusive; a visit could have multiple COVID-19 measures listed in the record. Data are based on a sample of 16,025emergency department visits by patients in 2022, representing about 155 million emergency department visits.

SOURCE: National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2022.

Figure 4 is a bar chart showing the percentages of emergency department visits with mentions of COVID-19 for 2022. Categories shown are any mention of COVID-19, confirmed COVID-19 case, COVID-19 test or screening, and other mentions of COVID-19.

Data table for Figure 4 Percentage of emergency department visits with mentions of COVID-19: United States, 2022

Measure | Percent | Standard error | 95% confidence interval
Any mention of COVID-19 | 25.2 | 1.3 | 22.8–27.9
Confirmed case | 4.8 | 0.5 | 3.9–5.8
Tested or screened | 22.8 | 1.2 | 20.5–25.3
Other mentions of COVID-19 | 2.8 | 0.5 | 2.0–4.0

NOTES: Categories are not mutually exclusive; a visit could have multiple COVID-19 measures listed in the record. Data are based on a sample of 16,025 emergency department visits by patients in 2022, representing approximately 155 million emergency department visits.

SOURCE: National Center for Health Statistics, National Hospital Ambulatory Medical Care Survey, 2022.

## Summary

In 2022, there were an estimated 155 million ED visits in the United States, with a total ED visit rate of 47 visits per 100 people. The ED visit rates for both infants younger than age 1 year and adults age 75 and older were higher than rates for all other age groups. The ED visit rate for Black people was higher than the rates for people of all other racial and ethnic groups that were considered. The ED visit rate for patients with Medicaid, CHIP, or other state-based programs was highest compared with all other sources of payment, and the rate for patients with private insurance was lowest. In 2022, 4.8% of all ED visits recorded a confirmed COVID-19 diagnosis. ED visits for COVID-19 testing or screening accounted for most visits that had a mention of COVID-19.

## Definitions

[underlined: COVID-19 measures]: These measures are not mutually exclusive—for example, a patient may have been coded as both a confirmed and tested case.

- Any mention of COVID-19: Consists of any of the measures listed in the following categories.
- Confirmed case of COVID-19: Consists of any listed diagnosis with International Classification of Diseases, 10th Revision, Clinical Modification (ICD–10–CM) code U07.1.
- Tested or screened for COVID-19: Consists of any listed diagnosis with ICD–10–CM code Z11.52, a visit involving a COVID-19 test or COVID-19 antibody test, and any mention of COVID-19 testing or screening in validated verbatim item notes or medication fields.
- Other mentions of COVID-19: Consists of any listed diagnosis with ICD–10–CM codes U09.9, Z20.822, Z86.16, and any other mention of COVID-19 in validated verbatim item notes or medication fields that did not mention testing or screening.

[underlined: ED visit rates]: Calculated by dividing the number of ED visits by estimates of the U.S. civilian noninstitutionalized population (developed by the U.S. Census Bureau’s Population Division) for selected characteristics including age group, sex, and race and ethnicity. Visit rates by patient’s primary expected source of payment are based on the patient’s primary expected payment source and proportional insurance data from the 2022 National Health Interview Survey, available from: https://www.cdc.gov/nchs/nhis/2022nhis.htm.

[underlined: Primary expected source of payment]: During data collection, all sources of payment were collected. For patients with more than one source of payment, the following hierarchy was used (with Medicare counted first and self-pay and no charge counted last) to combine payments into one mutually exclusive variable (primary expected source of payment):

- Medicare: Partial or full payment by a Medicare plan includes payments made directly to the hospital and payments reimbursed to the patient. Charges covered under a Medicare-sponsored prepaid plan are included.
- Medicaid: Partial or full payment by a Medicaid plan includes payments made directly to the hospital or reimbursed to the patient. Charges covered under a Medicaid-sponsored prepaid plan (health maintenance organization, for example), managed Medicaid, or CHIP and other state-based programs are included.
- Private: Partial or full payment by a private insurer (such as BlueCross BlueShield) includes payments made directly to the hospital or reimbursed to the patient. Charges covered under a private insurance-sponsored prepaid plan are included.
- Uninsured: Includes self-pay and no charge or charity. Self-pay is charges paid by the patient or patient’s family that will not be reimbursed by a third party. Self-pay includes visits for which the patient is expected to be ultimately responsible for most of the bill, even if the patient never actually pays it. This does not include copayments or deductibles. No charge or charity are visits for which no fee is charged (such as charity, special research, or teaching).
- Other: Includes worker’s compensation and other sources of payment not covered by the preceding categories, such as TRICARE, state and local governments, private charitable organizations, and other liability insurance (such as automobile collision policy coverage).

[underlined: Race and ethnicity]: Race and Hispanic ethnicity were collected separately, imputed, and converted into a single combined variable that includes Black non-Hispanic, White non-Hispanic, Hispanic, and other non-Hispanic races. Other races includes Asian, American Indian and Alaska Native, and Native Hawaiian or Other Pacific Islander people, and people of two or more races. Statistically reliable rates could not be calculated for the specific race and non-Hispanic groups included in other races. For 2022, 16.5% of weighted race data and 16.9% of weighted ethnicity data were missing for ED visits; race and ethnicity were imputed for these missing records. Race and ethnicity data were imputed on the data file using a model-based, single, sequential-regression imputation method. Missing race values were imputed to be Black, White, or Other. This decision was based on quality concerns with imputed estimates for race categories other than Black and White, based on research by an imputation work group (5). Hispanic ethnicity was imputed to be Hispanic or non-Hispanic.

## Data source and methods

Data for this report are from NHAMCS, an annual, nationally representative survey of nonfederal, general, and short-stay hospitals (4). NHAMCS provides data on the use and provision of ambulatory care services in hospital EDs. In 2022, the weighted NHAMCS response rate was 35%. Analyses for this report were conducted using data from a restricted-use data file. A public-use version of this file is available from: https://www.cdc.gov/nchs/ahcd/datasets_documentation_related.htm. Count estimates and measures of variance may differ between the restricted-use and public-use files. Information on accessing the restricted-use data file is available from: https://www.cdc.gov/rdc/index.htm. Data analyses were performed using the statistical packages SAS version 9.4 (SAS Institute, Cary, N.C.) and SAS-callable SUDAAN version 11.0 (RTI International, Research Triangle Park, N.C.). Two-tailed t tests with a significance level of p<0.05 were used to determine statistically significant differences between ED visit rates.

## About the authors

Christopher Cairns, Jill J. Ashman, and Kai Kang are with the National Center for Health Statistics, Division of Health Care Statistics.

## References

1 Cairns C, Kang K. National Hospital Ambulatory Medical Care Survey: 2022 emergency department summary tables. 2024. [Forthcoming].
2 National Center for Health Statistics. Percentage of two or more hospital emergency department visits in the past 12 months for children under age 18 years: United States, 2019–2022. Interactive summary health statistics for children—2019–2022. June 21, 2024.
3 National Center for Health Statistics. Percentage of having a hospital emergency department visit in past 12 months for adults aged 18 and over: United States, 2019–2022. Interactive summary health statistics for adults—2019–2022. June 21, 2024.
4 National Center for Health Statistics. 2022 NHAMCS micro-data file. 2024.
5 National Center for Health Statistics. 2022 NHAMCS micro-data file documentation. 2024. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/NHAMCS/doc22-ed-508.pdf.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Health Care Statistics

Carol J. DeFrances, Ph.D., Director

Alexander Strashny, Ph.D., Associate Director for Science

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/email-updates.htm.

For questions or general informationabout NCHS:

Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info

ISSN 1941–4927 Print ed.

ISSN 1941–4935 Online ed.

CS350580