# Introduction

Paid long-term care services and supports include a broad range of health, personal care, and support services that meet the needs of older people and other adults whose capacity for self-care is limited because of a chronic illness; injury; physical, cognitive, or mental disability; or other health-related conditions (1). Post-acute care provides rehabilitative or palliative services to patients just after a stay in an acute care hospital, or instead of a stay in an acute care setting. Depending on the intensity of care the patient requires, post-acute treatment may include a stay in a facility, outpatient services, or home care (2). Both post-acute and long-term care may be home- and community-based or provided in institutional care settings (1,3,4).

Previous versions of this report on long-term care (5) have focused on long-term care services and supports—adult day services centers, assisted living and similar residential care communities, home health agencies, hospices, and nursing homes. While the previous reports also covered some of the nation’s post-acute care services, including Medicare-certified skilled nursing facilities and home health agencies that provide both post-acute and long-term care, the results for these sectors were not a key focus (3).

This report provides an overview of the operational and user characteristics of seven paid, regulated post-acute and long-term care services providers in the United States. In addition to the sectors described in the previous report, this report expands the study’s representation of post-acute care by including two services providers that exclusively offer post-acute care: inpatient rehabilitation facilities and long-term care hospitals.

This report provides the only national statistics on adult day services centers and residential care communities in the United States, and a comprehensive comparison across key sectors in the post-acute and long-term care continuum. However, it does not represent the entire picture of post-acute and long-term care in the United States, which includes a large proportion of care provided by unpaid caregivers, such as family, friends, and neighbors. In 2015, 40 million people were unpaid caregivers of adults, which increased to 48 million in 2020 (6). Many of the older people and adults with disabilities who rely on the paid, regulated post-acute and long-term care services providers included in this report also receive care by unpaid caregivers. More information regarding unpaid caregivers and care recipients can be found in AARP and National Alliance for Caregiving’s 2020 report (6).

## Long-term Care Services

The Patient Protection and Affordable Care Act (ACA, P.L. 111-148, as amended, available from: https://www.govinfo.gov/content/pkg/PLAW-111publ148/pdf/PLAW-111publ148.pdf) uses the term “long-term services and supports” and defines it to include certain institutionally based and noninstitutionally based long-term services and supports [Section 10202(f)(1)]. This report uses “long-term care services” to refer to both health care-related and nonhealth care-related services.

Long-term care services include assistance with activities of daily living (ADLs; dressing, bathing, and toileting), instrumental activities of daily living (IADLs; medication management and housework), and health maintenance tasks. Long-term care services assist people in improving and maintaining an optimal level of physical functioning and quality of life and can include help from other people and special equipment or assistive devices. The need for long-term care services is generally defined based on functional limitations (need for assistance with or supervision in ADLs and IADLs) regardless of cause, age of the person, where the person is receiving assistance, whether the assistance is human or mechanical, and whether the assistance is paid or unpaid.

People may receive long-term care services in a variety of settings (4,7–9):

- In the community, such as at an adult day services center.
- In the home, for example, from a home health agency, hospice, or family and friends.
- In institutions, such as in a nursing home or skilled nursing facility.
- In other residential settings, such as in an assisted living or similar residential care community.

Long-term care services provided by paid regulated providers are an important component of personal health care spending in the United States (10). Estimates of expenditures for paid long-term care services vary, depending on what types of providers, populations, and services are included. Finding a way to pay for long-term care services is a growing concern for older adults, other people with disabilities, and their families, and it is a major challenge facing state and federal governments (11–14). People who use paid long-term care services, through home- and community-based services or institutional care, are among the most costly participants in Medicare and Medicaid programs (15). Medicaid finances the largest portion of paid long-term care services, followed by Medicare, out-of-pocket payments by persons and families, other private sources, private insurance, and other public programs (8,10,16).

Medicaid finances a variety of long-term care services through multiple mechanisms (such as Medicaid state plans, home- and community-based services waiver programs, and other options for community-based long-term care services), including an array of home- and community-based services and institutional services (17–19). Medicaid spending on long-term care services totaled $129 billion in 2018, accounting for 32% of total Medicaid expenditures (20). This report does not address all long-term care services financed by Medicaid. For example, intermediate care facilities for people with intellectual or developmental disabilities are excluded.

Decreasing family size and increasing employment rates among women may reduce the traditional pool of family caregivers, further stimulating demand for paid long-term care services (21). Among people who need long-term care services, adults aged 65 and over are more likely than younger adults to receive paid help (22). Results from the National Health and Aging Trends Study show that of the 10.9 million older adults who reported receiving help with daily activities in a given month in 2011, about 3 in 10 received paid help (23). Recent projections using microsimulation modeling estimate that about one-half of Americans reaching age 65 will need long-term care services and will incur, on average, $138,000 in long-term care costs (24). The average projected length of needing long-term care services is 2 years, including an average length of 1 year of paid long-term care services. However, about one-third of people turning age 65 are projected to need long-term care services for more than 2 years and to incur higher long-term care services costs (24).

## Post-acute Care Services

People may receive post-acute care services from home health agencies, skilled nursing facilities, inpatient rehabilitation facilities, and long-term care hospitals, all of which are included in this report. Users typically receive post-acute care following a hospitalization. In 2018, post-acute care fee-for-service spending was $58.6 billion (2). Post-acute care is a growing sector due to an increasing aging population with complex conditions, shorter hospital stays, and trends toward care coordination and community-based care (25). Medicare dictates specific criteria to cover beneficiaries in each post-acute care setting covered in this report.

Home health agencies provide nursing, therapeutic, and social work services to patients in their homes. It often replaces institutional post-acute care but can also be considered to provide long-term support services. This report includes Medicare- and Medicaid-participating home health agencies and beneficiaries. Post-acute home health care is typically covered by Medicare. Patients must be physician-certified for home health care and typically need part-time care and would have difficulty leaving the home (2).

This report includes Medicare and Medicaid-certified skilled nursing facilities, which offer short-term, post-acute nursing and rehabilitation care and are typically covered by Medicare, in addition to nursing homes that provide long-term services and supports. Nursing homes are often dual certified as a skilled nursing facility and nursing home to provide both levels of care. Skilled nursing facilities provide medical care, often through registered nurses (RNs), rehabilitation specialists, and medical doctors, where nursing homes provide more nonmedical support for ADLs (2).

Inpatient rehabilitation facilities must qualify for Medicare’s inpatient rehabilitation facility prospective payment system, and patients are enrolled in Medicare Part A fee-for-service. These facilities offer physical, occupational, and speech therapies and nursing services for patient rehabilitation after illness, injury, or surgery, usually following a hospital stay (2). In 2017, 75% of facilities were located within an acute care hospital and about 25% were freestanding; each setting is responsible for about one-half of inpatient rehabilitation facility discharges (2). Compared with Medicare requirements for skilled nursing facilities, participating inpatient rehabilitation facilities must have at least 60% of patients that meet certain guidelines to ensure inpatient rehabilitation facility admission, including being treated for one of 13 primary conditions (such as traumatic brain injury, spinal cord injury, amputation, congenital deformity, major burns, major trauma, orthopedic or arthritic conditions, joint replacement, hip fracture, and other neurological conditions) (26,27). Inpatient rehabilitation facility patients must require, and be likely to benefit from, resource-intensive inpatient care, medical supervision by a specially trained rehabilitation physician, a multidisciplinary team with a medical plan and 24-hour registered nurse care, and 3 hours of intensive therapy for 5 days a week (26,27).

Long-term care hospitals are for people with complex conditions who need hospital-level care for longer periods of time. This report includes long-term care hospitals that participate in the Medicare prospective payment system for long-term care hospitals and serve Medicare fee-for-service beneficiaries. They can be freestanding or hospital-based, must meet requirements for an acute care hospital, and their patients must have an average length of stay of more than 25 days (27). Long-term care hospital patients often require ventilators and have complex chronic comorbidities, organ failure, or severe infection (28). Compared with users of other types of post-acute care providers, such as skilled nursing and inpatient rehabilitation, long-term care hospital patients were more likely to have a preceding intensive care unit stay of a week or more (29).

Projections estimate that the number of older adults using paid post-acute and long-term care services will grow considerably in the coming years (21,30–33). A substantial share of these sectors are publicly funded through Medicare and Medicaid, and these sectors vary in the types of services they provide and in characteristics of the populations they serve. Accurate and timely statistical information can help guide public programs and inform relevant policy decisions, and the National Study of Long-Term Care Providers (NSLTCP) is designed to help supply this information.

National Study of Long-Term Care Providers

The post-acute and long-term care services delivery system in the United States has changed substantially over the last 30 years. For example, although nursing homes are still a major provider of long-term care services, use of skilled nursing facilities for short-term post-acute care and rehabilitation has increased (34). Additionally, consumers’ desire to stay in their own homes, as well as federal and state policy developments, have led to growth in a variety of home- and community-based alternatives (35–37). Examples of these federal and state policy developments include the U.S. Supreme Court’s Olmstead decision, introduction of the Medicare Prospective Payment System, and a variety of initiatives to encourage balancing of Medicaid-financed services from institutional to noninstitutional settings, such as Money Follows the Person, Community First Choice Option, and the Balancing Incentives Payment Program (38).

In 2011, the National Center for Health Statistics (NCHS) launched the biennial NSLTCP—an integrated strategy for efficiently obtaining and providing statistical information about the major sectors of paid, regulated long-term care services in the United States. The study began including post-acute care sectors in 2018. In 2020, the study was renamed National Post-acute and Long-term Care Study (NPALS) to reflect the addition of the two post-acute care sectors; however, this report refers to the 2018 study data as NSLTCP, the study’s name when the data were collected. NSLTCP is designed to provide reliable, accurate, relevant, and timely statistical information to support and inform post-acute and long-term care services policy, research, and practice.

The main goals of NSLTCP are to:

1. Estimate the supply, provision, and use of paid, regulated post-acute and long-term care services.
2. Estimate key policy-relevant characteristics and practices.
3. Produce national and state estimates, where feasible.
4. Compare estimates among sectors.
5. Monitor trends over time.

NSLTCP replaced NCHS’ periodic National Nursing Home Survey and National Home and Hospice Care Survey, as well as the onetime National Survey of Residential Care Facilities. Unlike the previous strategy of surveying major sectors of long-term care services separately and at different times—often several years apart—NPALS (formerly NSLTCP) provides information on providers and services users at similar points in time and provides updated information on all sectors every 2 years. The study is designed to:

- Broaden NCHS’ ongoing coverage of paid, regulated post-acute and long-term care services providers beyond home health agencies, hospices, and nursing homes to also include adult day services centers and assisted living and similar residential care communities (called “residential care communities” in this report).
- Have the potential over time to add other types of paid, regulated services providers.
- Capitalize on existing national administrative data from the Centers for Medicare & Medicaid Services (CMS).
- Collect primary data every other year from cross-sectional, nationally representative, establishment-based surveys of adult day services centers and residential care communities, because administrative data do not exist.
- Produce state estimates, where feasible.
- Compare and monitor trends across sectors.

In addition to the core content, the NPALS data collection system provides the infrastructure on which to build provider-specific surveys, cross-provider topical modules, more in-depth surveys to respond to evolving or emerging policy issues, and sampling and collecting information on individual users.

## Structure of Report

This is the fourth edition of a descriptive overview report intended to inform policy makers, providers, researchers, consumer advocates, the media, foundations, and others to inform planning for post-acute and long-term care services. The report includes two sections that present findings. “National Profile of Post-acute and Long-term Care Services Providers” presents findings on providers of post-acute and long-term care services. This section includes estimates on provider supply, geographical and organizational characteristics, staffing, and services offered.

In its 2008 report, “Retooling for an Aging America: Building the Health Care Workforce,” the Institute of Medicine documented the growing need for gerontological social workers and the lack of interest among social workers in working with older adults (39). According to one study, while 36,100–44,200 professional social workers were employed in long-term care settings in 2002, about 110,000 social workers would be needed in these settings by 2050 (40). Projections estimate that social workers and home health and personal care aides are among the long-term care services occupations that will grow the most by 2030 (41). This report contributes to the literature on the post-acute and long-term care services workforce by using NSLTCP data to provide information by sector on the numbers of nursing, licensed social work, and activities employees, and average hours per service user day.

The second section, “National Profile of Post-acute and Long-term Care Services Users,” presents findings on users, including participants of adult day services centers; patients of home health agencies, hospices, inpatient rehabilitation facilities, and long-term care hospitals; and residents of nursing homes and residential care communities. This section’s topics include demographic characteristics; functional status; selected health conditions, including Alzheimer disease and other dementias; and adverse events in services users, including hospitalizations and falls. Alzheimer disease is a common precipitating factor for transition to receiving long-term care services (42). According to the Alzheimer’s Association, in 2018 about 5.7 million Americans were living with Alzheimer dementia; 5.5 million of them were aged 65 and over (43). The number of people with Alzheimer disease or other dementias will continue to increase along with the growth of the older population (43). This section presents estimates on 10 diagnoses and overnight hospitalizations in nursing home residents and estimates by length of stay for selected characteristics (age, sex, race and ethnicity, diagnoses, overnight hospital stays, and falls) for nursing home residents.

The Technical Notes (Appendix I) describes the data sources used to produce the information on providers and services users in each of the seven sectors, outlines the approach used for data analyses, and discusses study limitations. Appendix II in this report defines each variable used for each sector in the study, and Appendix III presents the data tables for the figures in the report. This report presents national results from the fourth wave of NSLTCP, using data from surveys about adult day services centers and participants and residential care communities and residents that were fielded by NCHS between July 2018 and February 2019. The report also uses data from administrative records obtained from CMS on home health agencies and patients, hospices and patients, nursing homes and residents, inpatient rehabilitation facilities and patients, and long-term care hospitals and patients, which reflect these providers and services users from 2017 through 2018. See Appendix I for definitions of the seven sectors and the corresponding data sources used in this report. This report updates previous versions that are available from: https://www.cdc.gov/nchs/npals/studyresults.htm.