# National Profile of Post-acute and Long-term Care Services Users

Together, the seven post-acute and long-term care services sectors served almost 9.5 million (9,490,000) people in 2017 and 2018. This estimate is the sum of the estimates of the people served in each sector in one year (2017 or 2018) and is an approximation. Data used for each sector captured services users in different ways, and the year for the data used in each sector varied across sectors. The estimated number of adult day services center participants represents current participants on a given day in 2018. The estimated number of home health patients represents patients who ended care in 2017 (discharges). The estimated number of hospice, inpatient rehabilitation facility, and long-term care hospital patients represents Medicare beneficiaries who received care at any time in 2017. The estimated numbers of nursing home residents and residential care community residents each represent current residents on any given day in 2018. In this report, “current” participants or residents in 2018 refers to those participants enrolled in an adult day services center, or residents living in a nursing home or residential care community, on the day of the data collection in 2018, rather than the total number of participants ever enrolled in a center or residents ever living in a nursing home or residential care community at any time throughout the 2018 calendar year.

The same person may be included more than once in the sum of services users among the seven sectors if a person received care in more than one sector in a similar time period (such as a residential care resident receiving care from a home health agency). Given that the estimate for the number of current adult day center, nursing home, and residential care services users in a given day is likely to be less than the number of all services users in these sectors throughout that year, the estimate of all services users in all seven sectors as of 2018 is expected to be at least 9.5 million, despite the possibility of double-counting the same person across sectors.

In 2018, NCHS collected post-acute and long-term care user information about a sample of participants and residents in each of the centers and communities surveyed, which differs from data collection methods in the 2012, 2014, and 2016 surveys. See Appendix I for more information on data collection of services users and the data sources used for each sector.

In 2018, an estimated 251,100 current participants were enrolled in adult day services centers and 918,700 current residents were living in residential care communities (Appendix III, Table XII). Nursing home resident information is based on two data sources from CMS. The estimated overall number of residents are from the Certification and Survey Provider Enhanced Reports (CASPER) nursing home data source, but the number of nursing home residents by length of stay are from the Minimum Data Set Active Resident Episode Table (MARET), resulting in a difference between the estimated overall total number of residents (Appendix III, Table XII) and number of residents by length of stay (Appendix III, Table XIII) (see Appendix I for more information about nursing home resident data). About 1,321,200 current residents were reported in CASPER, and of the 1,372,500 current residents reported in MARET, 598,700 (43%) had a stay of fewer than 100 days (short stay) and 773,800 (57%) had a stay of 100 days or longer (long stay) (Appendix III, Table XIII). In 2017, about 4,940,300 patients received services and were discharged from home health agencies, and 1,562,500 patients received services from hospices. About 380,400 patients received services at inpatient rehabilitation facilities, and 115,800 patients received services at long-term care hospitals (Appendix III, Table XII).

This section provides an overview of the demographic, health, and functional composition of users of post-acute and long-term care services, and their experience of adverse events, by sector. Demographic measures include age, race and ethnicity, and sex. Medicaid as a payer source is used to measure payment characteristics. Measures of health status include diagnoses of Alzheimer disease and other dementias, arthritis, asthma, chronic kidney disease, chronic obstructive pulmonary disease (COPD), depression, diabetes, heart disease, high blood pressure or hypertension, and osteoporosis. Measures of functional status include needing assistance with selected activities of daily life (ADLs) (bathing, dressing, toileting, walking or locomotion, transferring in and out of a chair or bed, and eating). Measures of adverse events include overnight hospital stays, emergency department visits, and falls.

## Use of Post-acute and Long-term Care Services

Given the data available, daily-use rates were compared for adult day services center participants, nursing home residents, and residential care community residents, while annual-use rates were compared for home health agency, hospice, inpatient rehabilitation facility, and long-term care hospital patients. Use of services by people aged 65 and over per 1,000 people aged 65 and over varied by sector. The daily-use rate was higher for nursing homes (21 per 1,000), compared with residential care communities (16 per 1,000) and adult day services centers (3 per 1,000). The annual-use rate was higher for home health agencies (78 per 1,000) compared with hospices (28 per 1,000), inpatient rehabilitation facilities (6 per 1,000), and long-term care hospitals (2 per 1,000).

## Demographic Characteristics of Post-acute and Long-term Care Services Users

### Services users by age

Most services users were aged 65 and over: 94.8% of hospice patients, 92.5% of residential care residents, 87.9% of inpatient rehabilitation patients, 83.1% of nursing home residents, 82.6% of home health patients, 74.3% of long-term care hospital patients, and 60.5% of participants in adult day services centers (Figure 20). Among nursing home residents, 81.1% of short-stay residents and 84.6% of long-stay residents were aged 65 and over (Appendix III, Table XIII).

The age composition of services users varied by sector, with residential care communities (54.9%), hospices (48.0%), and nursing homes (36.4%) serving more people aged 85 and over, and adult day services centers (39.4%) and long-term care hospitals (25.7%) serving more people under age 65 than other sectors. Among nursing home residents, 30.7% of short-stay residents and 40.9% of long-stay residents were aged 85 and over (Appendix III, Table XIII).

### Services users by sex

In all sectors except long-term care hospitals, where 51.8% of patients were men, the majority of users were women, with residential care communities having the highest percentage (67.4%) (Figure 21). Among nursing home residents, 59.0% of short-stay residents and 66.6% of long-stay residents were women (Appendix III, Table XIII).

Figure 21 Percent distribution of post-acute and long-term care services users, by sector and sex: United States, 2017 and 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 21 is a stacked bar chart showing percent distribution of post-acute and long-term care services users by sector and sex in the United States in 2017 and 2018.

### Services users by race and ethnicity

The percentage of non-Hispanic White people was highest in residential care communities (89.4%), followed by hospices (82.3%), inpatient rehabilitation facilities (79.9%), home health agencies (76.8%), nursing homes (73.9%), and long-term care hospitals (66.3%) (Figure 22). Less than one-half of the participants in adult day services centers were non-Hispanic White (44.8%). Adult day services centers were the most racially and ethnically diverse among the seven sectors: 16.8% of center participants were non-Hispanic Black and 22.2% were Hispanic. Long-term care hospitals (19.8%), adult day services centers (16.8%), and nursing homes (14.9%) had the highest percentage of non-Hispanic Black services users. About one-tenth of home health patients (12.1%), inpatient rehabilitation facility patients (10.8%), hospice patients (8.3%), and residential care residents (5.9%) were non-Hispanic Black. In nursing homes, 73.3% of short-stay residents and 74.4% of long-stay residents were non-Hispanic White, followed by non-Hispanic Black (14.6% and 15.2% of short- and long-stay residents, respectively) (Appendix III, Table XIII).

### Services users by use of Medicaid as a payer source

The percentage of services users using Medicaid as a payer source was highest in adult day services centers (72.3%) and nursing homes (62.0%) (Figure 23). Among residential care residents, 18.1% used Medicaid as a payer source, followed by 9.1% of home health patients. Data on Medicaid as payer source were not available for hospice, inpatient rehabilitation, and long-term care hospital patients.

Figure 23 Percentage of post-acute and long-term care services users with Medicaid as payer source, by sector: United States, 2017 and 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 23 is a bar chart showing percentage of post-acute and long-term care services users with Medicaid as payer source by sector in the United States in 2017 and 2018.

### Health and Functional Characteristics of Post-acute and Long-term Care Services Users

#### Diagnosed chronic conditions in services users

Alzheimer disease or other dementias were most prevalent in nursing home residents (49.1%), followed by hospice patients (46.3%) and long-term care hospital patients (45.5%), and were least prevalent in adult day services center participants (27.8%) (Figure 24). The percentage of nursing home residents with a diagnosis of Alzheimer disease was higher in long-stay residents (57.6%) than short-stay residents (35.8%) (Appendix III, Table XIII). Arthritis was most prevalent in patients in inpatient rehabilitation facilities (62.8%), followed by home health patients (61.7%), and was least prevalent in adult day participants (18.5%) (Appendix III, Table XII). The percentage of services users with a diagnosis of asthma was highest in long-term care hospital patients (13.9%) and lowest in residential care community residents (2.0%). A diagnosis of chronic kidney disease was most common in long-term care hospital patients (81.4%) and least common in adult day services center participants (5.7%) and residential care community residents (6.5%). Similarly, COPD was most common in long-term care hospital patients (55.4%) and least prevalent in adult day services center participants (6.8%).

The percentage of services users with a diagnosis of depression was highest in long-term care hospitals (51.8%), followed by inpatient rehabilitation facilities (49.2%) and nursing homes (48.8%), and lowest in adult day centers (21.8%) and hospices (23.7%) (Figure 24). In nursing home residents, the prevalence of a diagnosis of depression was higher in long-stay residents (52.7%) than short-stay residents (42.8%) (Appendix III, Table XIII). A diagnosis of diabetes was most prevalent in long-term care hospital patients (64.2%) and least prevalent in residential care community residents (20.4%). A diagnosis of heart disease was most common in long-term care hospital patients (68.3%), followed by patients in inpatient rehabilitation facilities (59.8%) and home health patients (54.4%). More than one-half of services users in all seven sectors had a diagnosis of hypertension, with the highest percentage in patients in inpatient rehabilitation facilities (93.6%) and long-term care hospitals (93.5%), followed by home health care patients (89.2%). The percentage of services users with a diagnosis of osteoporosis was highest in inpatient rehabilitation facilities (17.4%) and lowest in hospices (6.4%).

#### Need for assistance with ADLs in services users

This report uses the need for assistance with six ADLs—bathing, dressing, toileting, walking or locomotion, transferring in and out of a chair or bed, and eating—to measure physical and cognitive functioning in adult day services center participants, home health patients, residents in nursing homes and residential care communities, and inpatient rehabilitation facility patients. Data on need for assistance with ADLs were not available for hospice patients and long-term care hospital patients.

Overall, functional ability varied by sector (Figure 25). Within each sector, the need for assistance with bathing was most common. Fewer adult day services center participants needed assistance with bathing (74.8%) compared with services users in the other four sectors. Therefore, while the prevalence of ADL needs differed by sector, at minimum, 74.8% of services users across all sectors needed assistance with at least one of the six ADLs. The need for assistance with eating was least common in each of the five sectors. Residential care communities had the fewest residents that needed assistance with dressing, toileting, transferring in and out of bed or chair, and eating than services users in other sectors. Nearly all patients in inpatient rehabilitation facilities needed assistance with bathing, dressing, toileting, locomotion, and transferring.

#### Adverse events in services users

This report estimates the prevalence of overnight hospitalizations, emergency department visits, and falls as indicators of adverse, potentially avoidable events. For adult day services centers and residential care communities, adverse event refers to a period of 90 days before the survey. For home health agencies, adverse event refers to a period since the last Outcome and Assessment Information Set (OASIS) assessment. For nursing homes, overnight hospitalization and fall refer to the period since admission or since the prior assessment, whichever is more recent. Varying reference periods by sector do not allow for direct comparisons between sectors.

Similar percentages of home health patients had overnight hospital stays (15.0%) and emergency department visits (16.1%) (Figure 26). About 14.6% of nursing home residents had overnight hospital stays; more short-stay residents had overnight hospital stays (23.0%) than long-stay residents (8.2%) (Appendix III, Table XIII). About 7.7% of residential care community residents and 5.4% of adult day services center participants had overnight hospital stays. About 9.7% of adult day services center participants and 12.1% of residential care residents had emergency department visits. About 29.6% of residential care community residents, 17.0% of nursing home residents, and 14.4% of adult day services center participants had falls. More long-stay nursing home residents (19.3%) than short-stay residents (13.5%) had falls. For home health patients, data for falls were not available. For nursing home residents, data for emergency department visits were not available. For hospice patients, long-term care hospital patients, and patients in inpatient rehabilitation facilities, data for emergency department visits, overnight hospital stays, and falls were not available.