# National Profile of Post-acute and Long-term Care Services Providers

## Supply of Post-acute and Long-term Care Services Providers

As of 2018, there were an estimated 4,200 adult day services centers, 11,500 home health agencies, 4,700 hospices, 15,600 nursing homes, 31,400 residential care communities, 1,200 inpatient rehabilitation facilities, and 400 long-term care hospitals in the United States (Appendix III, Table IX). This report includes only providers that are in some way regulated by federal or state government. Adult day services centers and residential care communities were state regulated; home health agencies, inpatient rehabilitation facilities, long-term care hospitals, and nursing homes were Medicare- or Medicaid-certified; and hospices were Medicare-certified. Of these estimated 69,000 paid, regulated post-acute and long-term care services providers, 6.1% were adult day services centers, 16.7% were home health agencies, 6.8% were hospices, 22.6% were nursing homes, 45.5% were residential care communities, 1.7% were inpatient rehabilitation facilities, and 0.6% were long-term care hospitals.

This section provides an overview of the supply, organizational characteristics, staffing, and services offered by paid, regulated providers of post-acute and long-term care services in each of these seven sectors. Supply information is provided nationally, by census geographic region, by metropolitan statistical area (MSA) status, and by capacity. Organizational characteristics include ownership type, chain affiliation, Medicare and Medicaid certification, and number of people served. Staffing measures include number and distribution of nursing and social work employees; percentage of providers employing any nursing, social work, or activities employees; and average hours per resident or participant per day, by staff type. Services include social work; mental health or counseling; physical, occupational, and speech; skilled nursing or nursing; pharmacy or pharmacist; hospice; dietary and nutritional; and dementia care.

### Geographic distribution

The supply of providers in the seven post-acute and long-term care services sectors varied in their geographic distribution. The largest share of adult day services centers (33.3%), home health agencies (43.9%), hospices (37.4%), nursing homes (34.9%), inpatient rehabilitation facilities (41.3%), and long-term care hospitals (54.6%) was in the South, while the largest share of residential care communities (40.2%) was in the West (Figure 1).

Figure 1 Percent distribution of post-acute and long-term care services providers, by sector and region: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 1 is a stacked bar chart showing percent distribution of post-acute and long-term care services providers by sector and region in the United States in 2018.

Metropolitan and micropolitan statistical areas (MSAs) are geographic entities defined by the Office of Management and Budget (see Appendix II for MSA definition). Most providers in all seven sectors were in MSAs (Figure 2). This distribution reflects the higher population density in these areas. Compared with hospices (81.1%) and nursing homes (71.9%), a greater percentage of long-term care hospitals (94.8%), inpatient rehabilitation facilities (86.7%), residential care communities (86.5%), home health agencies (85.4%), and adult day services centers (84.6%), were in MSAs.

Figure 2 Percent distribution of post-acute and long-term care services providers, by sector and metropolitan statistical area status: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 2 is a stacked bar chart showing percent distribution of post-acute and long-term care services providers by sector and metropolitan statistical area status in the United States in 2018.

### Capacity

Based on the maximum number of participants allowed, the 4,200 adult day services centers in the country could serve a daily maximum of up to 283,200 participants nationally (Appendix III, Table IX). The allowable daily capacity of adult day services centers ranged from 1 to 400, with an average capacity of 68 participants. The 15,600 nursing homes in the country provided a total of 1,655,400 certified beds. Nursing homes ranged in capacity from 2 to 1,389 certified beds, with an average of 106 certified beds. The 31,400 residential care communities in the United States provided 1,183,600 licensed beds. Residential care communities ranged in capacity from 4 to 418 licensed beds, with an average of 38 licensed beds. The 1,200 inpatient rehabilitation facilities provided a total of 344,600 certified beds. Inpatient rehabilitation facilities ranged in capacity from 10 to 2,449 beds, with an average of 298 licensed beds. The 400 long-term care hospitals had a total of 26,500 licensed beds. Long-term care hospitals ranged in capacity from 4 to 760 licensed beds with an average of 68 licensed beds. Capacity for home health agencies and hospices was not examined because licensed maximum capacity or a similar metric was not available.

The supply of adult day services center capacity and nursing home, residential care, inpatient rehabilitation facility, and long-term care hospital beds varied by region (Figure 3). Compared with other regions, the Midwest had the largest supply of nursing home beds (42) and the smallest supply of adult day services center capacity (3) per 1,000 people aged 65 and over. The Midwest (29) and West (27) had a larger supply of residential care beds per 1,000 people aged 65 and over compared with the Northeast (19) and the South (18). In the West, the supply of residential care beds (27) was greater than the supply of nursing home beds (20) per 1,000 people aged 65 and over, while nursing home beds outnumbered residential care beds in all other regions. The West had the smallest supply of inpatient rehabilitation (5) and long-term care hospital (0.3) capacity per 1,000 people aged 65 and over compared with other regions.

## Organizational Characteristics of Post-acute and Long-term Care Services Providers

### Ownership type

In all sectors except adult day services centers and inpatient rehabilitation facilities, most post-acute and long-term care services providers were for profit (Figure 4). Home health agencies (82.0%) and residential care communities (79.2%) had the highest percentages of for-profit ownership, while inpatient rehabilitation facilities (34.4%) and adult day services centers (42.3%) had the lowest percentages. About one-half of adult day services centers (52.8%) and 46.9% of inpatient rehabilitation facilities were nonprofit.

### Chain status

The majority of residential care communities (60.3%) and nursing homes (58.6%) were chain-affiliated, while fewer adult day services centers (42.7%) were part of a chain (Figure 5). Chain affiliation for home health agencies, hospices, inpatient rehabilitation facilities, and long-term care hospitals was not examined because this information was not available.

### Medicare and Medicaid certification

All data on home health agencies, nursing homes, inpatient rehabilitation facilities, and long-term care hospitals used in this report are only for Medicare- or Medicaid-certified providers, and all data on hospices are only for Medicare-certified hospices. Virtually all inpatient rehabilitation facilities (100%), long-term care hospitals (100%), home health agencies (98.6%), and nursing homes (95.4%) were Medicare-certified (Figure 6). Medicare does not pay for adult day care services or for the cost of residency and care in residential care communities, so they were not asked about Medicare certification. Almost all inpatient rehabilitation facilities (95.9%) and nursing homes (95.4%); about three-quarters of adult day services centers (74.9%), home health agencies (78.9%), and long-term care hospitals (76.9%); and almost one-half of residential care communities (46.9%) were authorized or certified to participate in Medicaid. Information was not available on whether any Medicare-certified hospices were also certified by Medicaid.

Figure 6 Percentage of post-acute and long-term care services providers that are Medicare- and Medicaid-certified, by sector: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 6 is a bar chart showing percentage of post-acute and long-term care services providers that are Medicare- and Medicaid-certified by sector in the United States in 2018.

### Number of people served

See Appendix II for how the number of people served was defined for each sector.

In terms of people served daily per provider, nursing homes served, on average, more than twice the number of people as residential care communities. Nursing homes had an average of 85 current residents daily, while adult day services centers had an average weekday daily attendance of 65 participants, and residential care communities served an average of 32 residents daily (Appendix III, Table IX).

The majority of adult day services centers (58.7%) and nursing homes (65.4%) served between 26 and 100 residents daily, while the majority of residential care communities (62.9%) served 25 residents or fewer daily (Figure 7). The percentage of nursing homes serving more than 100 people daily (29.1%) was almost five times higher than the percentage of residential care communities (6.0%) doing so, and about 1.5 times higher than the percentage of adult day services centers (18.5%) doing so (Figure 7).

Figure 7 Percent distribution of post-acute and long-term care services providers, by sector and number of people served daily: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 7 is a stacked bar chart showing percent distribution of post-acute and long-term care services providers by sector and number of people served daily in the United States in 2018.

In terms of people served annually, in 2017, home health agencies served an average of 458 patients (who were then discharged from the agency in 2017), hospices served an average 356, inpatient rehabilitation facilities served an average 348, and long-term care hospitals served an average 293 (Appendix III, Table IX).

About 42.7% of home health agencies discharged 100 patients or fewer annually, while 24.4% discharged 101–300, and 32.9% discharged 301 or more (Figure 8). The number of patients served annually per hospice agency was about evenly distributed, with about one-third of agencies each serving 1–100 patients (37.1%), 101–300 (32.5%), and 301 or more (30.3%). For inpatient rehabilitation facilities, 15.0% served 100 or fewer patients, 46.2% served 101–300 patients, and 38.8% served more than 300 patients. More than one-half of long-term care hospitals served 101–300 patients (58.3%), about one-third (32.6%) served more than 300 patients, and 9.1% served 1–100 patients.

Figure 8 Percent distribution of post-acute and long-term care services providers, by sector and number of people served annually: United States, 2017

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 8 is a stacked bar chart showing percent distribution of post-acute and long-term care services providers by sector and number of people served annually in the United States in 2018.

## Staffing: Nursing, Social Work, and Activities Employees

This section focuses on workers employed directly by adult day services centers, home health agencies, hospices, nursing homes, residential care communities, inpatient rehabilitation facilities, and long-term care hospitals. Information is provided about RNs, licensed practical nurses (LPNs) or licensed vocational nurses (LVNs), aides, social workers, and activities staff. See Appendix II for the definition of FTE and each staff type used for each sector. Contract staff who work for these providers were excluded because comparable information on contract staff was not available for all seven sectors.

### Nursing and social work employee FTEs

All seven sectors employed nursing FTEs, including RNs and LPNs or LVNs; adult day services centers, home health agencies, hospices, nursing homes, and residential care communities also employed aides and social workers. Inpatient rehabilitation facilities and long-term care hospitals did not employ aides and social workers. In 2018, about 1,632,700 nursing employee FTEs worked in the seven sectors, and about 33,700 social work employee FTEs worked in the five sectors that employed social workers (data not shown). Of these nursing and social work employees, 39.6% (660,000 FTEs) were nursing home employees, 28.5% (474,200 FTEs) were residential care community employees, 15.8% (263,900 FTEs) were inpatient rehabilitation facility employees, 8.4% (139,200 FTEs) were employed by home health agencies, 5.5% (91,300 FTEs) were employed by hospices, 1.5% (24,300 FTEs) were adult day services center employees, and 0.8% (13,600 FTEs) were employed by long-term care hospitals (Appendix III, Table X).

The relative distribution of social work and nursing employee FTEs varied across sectors. The majority of employee FTEs in adult day centers (55.6%), nursing homes (62.8%), and residential care communities (70.0%) were aides (Figure 9). However, in inpatient rehabilitation facilities (92.4%), long-term care hospitals (79.9%), home health agencies (51.5%), and hospices (48.4%), RNs were the most common employee FTEs. Social work FTE employees were most common in hospices (11.3%), followed by adult day services centers (9.3%), home health agencies (2.6%), nursing homes (1.8%), and residential care communities (1.2%).

The administrative data used in this report for the home health, hospice, and nursing home sectors used less-inclusive wording to capture aides than was used in the questionnaire data for adult day services centers and residential care communities. Consequently, estimates using the administrative data may undercount the number of aides employed by providers in those sectors. See Appendix II for how aide was defined for each sector.

### Providers employing any nursing, social work, or activities staff

Among the different staff types, RNs and LPNs or LVNs were employed in all seven sectors. Aides and social workers were employed in five sectors: adult day services centers, home health agencies, hospices, nursing homes, and residential care communities.

Most providers in all sectors except residential care communities employed licensed nursing staff (RNs and LPNs or LVNs). Virtually all home health agencies (99.6%), hospices (100.0%), inpatient rehabilitation facilities (97.6%), and long-term care hospitals (96.9%) employed at least one RN (Figure 10). In contrast, 71.4% of nursing homes, 61.0% of adult day services centers, and 41.9% of residential care communities directly employed at least one RN. Most inpatient rehabilitation facilities (87.3%), long-term care hospitals (76.2%), home health agencies (72.8%), nursing homes (70.9%), and hospices (65.1%) employed at least one LPN or LVN, while a minority of adult day services centers (41.4%) and residential care communities (41.3%) directly employed at least one LPN or LVN.

Figure 10 Percentage of post-acute and long-term care services providers with any full-time equivalent employees, by sector and staff type: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 10 is a bar chart showing percentage of post-acute and long-term care services providers with any full-time equivalent employees by sector and staff type in the United States in 2018.

Among the four staff types (RNs, LPNs or LVNs, aides, and social workers) examined across the five sectors where they were employed, most providers employed aides: hospices (97.8%) were most likely and adult day services centers (65.2%) were least likely to have any aides on staff. Use of aide staff was not examined for inpatient rehabilitation centers or long-term care hospitals because this information was not available.

Employing any social workers showed the most variation across the five sectors where they were employed. Virtually all hospices employed social workers (99.2%), as did most nursing homes (55.7%). About 46.7% of home health agencies and 37.1% of adult day services centers employed social workers, but only 13.0% of residential care communities directly employed social workers. Use of social worker staff was not examined for inpatient rehabilitation facilities or long-term care hospitals because this information was not available.

Most adult day services centers (80.5%), nursing homes (69.7%), and residential care communities (56.7%) directly employed an activities director or activities staff. Use of activities staff was not examined for home health agencies, hospices, inpatient rehabilitation facilities, or long-term care hospitals because this information was not available.

### Staffing hours for nursing, social work, and activities staff

To provide a measure by which to compare staffing levels across sectors, hours per user (resident or participant) per day are provided in this report. See Appendixes I and II for details on how hours per resident or participant per day were computed for adult day services centers, nursing homes, and residential care communities. Hours per patient per day could not be provided for home health agencies, hospices, inpatient rehabilitation facilities, or long-term care hospitals because the administrative data available provided the total number of all patients served in a year rather than the number served on a given day, which is needed to produce this estimate.

For both licensed nursing staff types examined (RN and LPN or LVN), the average staff hours per resident or participant per day was higher in residential care communities than in nursing homes and adult day services centers (Figure 11). The average total nursing hours (combining RNs, LPNs or LVNs, and aides) per resident or participant per day was 3.45 (3 hours and 27 minutes) for residential care community residents, 2.65 (2 hours and 39 minutes) for nursing home residents, and 1.20 (1 hour and 12 minutes) for adult day participants. The average total nursing hours per resident per day in adult day services centers was one-half the size of the ratio for nursing homes and less than one-third for residential care communities.

The average total licensed nursing hours (combining RNs with LPNs or LVNs) per resident or participant per day was 1.17 (1 hour and 10 minutes) for residential care community residents, 0.98 (59 minutes) for nursing home residents, and 0.46 (28 minutes) for adult day participants. The average total licensed nursing hours per resident or participant per day in residential care communities was almost three times the size of the corresponding ratio for adult day services centers.

The average social work staff hours per resident or participant per day was similar in residential care communities (0.06 hours, or 4 minutes) and in adult day services centers (0.08 hours, or 5 minutes) and nursing homes (0.06 hours, or 4 minutes). The average activities staff hours per resident or participant per day in adult day services centers (0.63 hours, or 38 minutes) was more than residential care communities (0.39 hours, or 23 minutes) or nursing homes (0.14 hours, or 8 minutes).

## Services Provided

This section provides information on what percentage of providers in each sector (where data were applicable and available) offered each of seven services: social work, mental health or counseling, therapies (physical, occupational, and speech), skilled nursing or nursing, pharmacy or pharmacist, hospice, and dietary and nutrition. Services could be provided directly by the provider or by others through arrangements made by the provider (Appendix III, Table XI). These seven services were chosen because they are commonly provided by Medicare- and Medicaid-certified long-term care services providers, and administrative data were available for most sectors. However, the available administrative data did not have information on whether home health agencies, inpatient rehabilitation facilities, or long-term care hospitals provided mental health or counseling services, or on whether hospices provided pharmacy or pharmacist services. Data on inpatient rehabilitation facilities and long-term care hospitals also did not have information about skilled nursing and hospice services. In addition to the seven services listed, the provision of dementia care units is also included. See Appendix II for definitions of services included for each sector.

As was done for the 2014 and 2016 adult day and residential care community questionnaires—but in contrast to the 2012 adult day and residential care community questionnaires—for each service in the 2018 questionnaires, if an adult day services center or residential care community reported offering only referrals to participants or residents, respectively, the provider was considered as not providing the service. See Appendix I for more information on differences in how services were measured in 2012 compared with the 2014, 2016, and 2018 adult day and residential care community measurements.

### Social work services

Most providers in all sectors offered social work services (Figure 12). All hospices provided social work services (100.0%), as did most inpatient rehabilitation facilities (97.5%), long-term care hospitals (88.2%), home health agencies (81.7%), and nursing homes (63.8%), likely because providing these services is required for Medicare certification. A majority of residential care communities (62.8%) provided social work services, but fewer adult day services centers (50.2%) did so.

Figure 12 Percentage of post-acute and long-term care services providers that provide social work services, by sector: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 12 is a bar chart showing percentage of post-acute and long-term care services providers that provide social work services by sector in the United States in 2018.

### Mental health or counseling services

Mental health or counseling services were offered by most hospices (97.3%) and a majority of nursing homes (63.6%) and residential care communities (62.0%), while just over one-third of adult day services centers (37.7%) reported offering these services (Figure 13).

Figure 13 Percentage of post-acute and long-term care services providers that provide mental health or counseling services, by sector: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 13 is a bar chart showing percentage of post-acute and long-term care services providers that provide mental health or counseling services by sector in the United States in 2018.

### Therapeutic services

Virtually all inpatient rehabilitation facilities (99.8%), long-term care hospitals (99.5%), hospices (97.9%), and home health agencies (95.8%) offered therapeutic services, as did more than seven-tenths of residential care communities (71.7%) and nursing homes (71.7%) and almost one-half of adult day services centers (45.4%) (Figure 14).

Figure 14 Percentage of post-acute and long-term care services providers that provide any therapeutic services, by sector: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 14 is a bar chart showing percentage of post-acute and long-term care services providers that provide any therapeutic services by sector in the United States in 2018.

### Skilled nursing or nursing services

All home health agencies and hospices (100.0%) offered skilled nursing or nursing services, as did most nursing homes (71.6%), residential care communities (70.8%), and adult day services centers (62.0%) (Figure 15).

Figure 15 Percentage of post-acute and long-term care services providers that provide skilled nursing or nursing services, by sector: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 15 is a bar chart showing percentage of post-acute and long-term care services providers that provide skilled nursing or nursing services by sector in the United States in 2018.

### Pharmacy or pharmacist services

Nearly all inpatient rehabilitation facilities (99.0%) and long-term care hospitals (98.0%) and most residential care communities (84.5%) and nursing homes (70.1%) offered pharmacy or pharmacist services. Fewer adult day services centers (30.9%) and home health agencies (4.5%) provided these services (Figure 16).

Figure 16 Percentage of post-acute and long-term care services providers that provide pharmacy or pharmacist services, by sector: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 16 is a bar chart showing percentage of post-acute and long-term care services providers that provide pharmacy or pharmacist services by sector in the United States in 2018.

### Hospice services

About 83.0% of nursing homes offered hospice services, compared with 66.8% of residential care communities, 12.6% of adult day services centers, and 5.4% of home health agencies (Figure 17).

Figure 17 Percentage of post-acute and long-term care services providers that provide hospice services, by sector: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 17 is a bar chart showing percentage of post-acute and long-term care services providers that provide hospice services by sector in the United States in 2018.

### Dietary and nutritional services

Nearly all inpatient rehabilitation facilities (98.8%) and long-term care hospitals (96.4%) and most residential care communities (82.6%) and nursing homes (71.5%) offered dietary and nutritional services, while 60.5% of adult day services centers provided these services (Figure 18).

Figure 18 Percentage of post-acute and long-term care services providers that provide dietary and nutritional services, by sector: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 18 is bar chart showing percentage of post-acute and long-term care services providers that provide dietary and nutritional services by sector in the United States in 2018.

### Dementia care units

About 19.4% of residential care communities and 13.4% of nursing homes offered a dementia care unit within a larger facility or community (Figure 19). While another 6.0% of residential care communities served only residents with dementia, few nursing homes (0.3%) did so. Dementia care units or dementia-only providers were not examined for adult day services centers, home health agencies, hospices, inpatient rehabilitation facilities, or long-term care hospitals because these topics are more relevant for residential sectors, such as nursing homes and residential care communities.

Figure 19 Percent distribution of post-acute and long-term care services providers, by sector and dementia care: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 19 is a stacked bar chart showing percent distribution of post-acute and long-term care services providers by sector and dementia care in the United States in 2018.