# References

1 Association for Community Living. LongTermCare.gov. Available from: https://acl.gov/ltc/basic-needs/.
2 Medicare Payment Advisory Commission (MedPAC). March 2020 report to the Congress: Medicare payment policy. Available from: https://www.medpac.gov/document/http-www-medpac-gov-docs-default-source-reports-mar20_entirereport_sec-pdf/.
3 Goldberg TH. The long-term and post-acute care continuum. W V Med J 112(3);68–74. 2016. Available from: https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4476054/.27301158
4 Genworth. Cost of Care Survey: Summary and methodology. 2022. Available from: https://pro.genworth.com/riiproweb/productinfo/pdf/131168.pdf.
5 Harris-Kojetin L, Sengupta M, Lendon JP, Rome V, Valverde R, Caffrey C. Long-term care providers and services users in the United States, 2015–2016. National Center for Health Statistics. Vital Health Stat 3(43). 2019.
6 AARP, National Alliance for Caregiving. Caregiving in the United States 2020. Washington, DC: AARP. 2020. Available from: https://doi.org/10.26419/ppi.00103.001.
7 Harrington C, Wiener JM, Ross L, Musumeci M. Key issues in long-term services and supports quality. Kaiser Family Foundation. 2017. Available from: https://www.kff.org/medicaid/issue-brief/key-issues-in-long-term-services-and-supports-quality/.
8 Nguyen V. Fact sheet: Long-term support and services. AARP Public Policy Institute. 2017. Available from: https://www.aarp.org/content/dam/aarp/ppi/2017-01/Fact%20Sheet%20Long-Term%20Support%20and%20Services.pdf.
9 Wiener JM, Lepore M, Jones J. What policymakers need to know about long-term services and supports. Public Policy Aging Rep 28(1):29–34. 2018.
10 O’Shaughnessy C. The basics: National spending for long-term services and supports (LTSS). 2011. Available from: https://collections.nlm.nih.gov/master/borndig/101561786/National%20Sepnding%20Long_Term%20Services%202011.pdf.
11 Anthony S, Traub A, Lewis S, Mann C, Kruse A, Soper MH, Somers SA. Strengthening Medicaid long-term services and supports in an evolving policy environment: A toolkit for states. 2019. Available from: https://www.chcs.org/resource/strengthening-medicaid-long-term-services-supports-evolving-policy-environment-toolkit-states/.
12 Bipartisan Policy Center. Financing long-term services and supports: Seeking bipartisan solutions in politically challenging times. 2017. Available from: https://bipartisanpolicy.org/wp-content/uploads/2019/03/BPC-Health-Financing-Long-Term-Services-and-Supports.pdf.
13 The AARP Foundation, The Commonwealth Fund, The Scan Foundation, AARP. Raising expectations: A state scorecard on long-term services and supports for older adults, people with physical disabilities, and family caregivers. Available from: https://www.longtermscorecard.org.
14 U.S. Senate Commission on Long-Term Care. Commission on long-term care: Report to the Congress. 2013. Available from: https://digital.library.unt.edu/ark:/67531/metadc307520/.
15 Newcomer RJ, Ko M, Kang T, Harrington C, Hulett D, Bindman AB. Health care expenditures after initiating long-term services and supports in the community versus in a nursing facility. Med Care 54(3):221–8. 2016.26759982
16 Colello KJ, Girvan GA, Mulvey J, Talaga SR. Long-term services and supports: Overview and financing. Congressional Research Service Report R42345. 2012. Available from: https://www.hsdl.org/?abstract&did=707282.
17 Kaiser Commission on Medicaid and the Uninsured. How is the Affordable Care Act leading to changes in Medicaid long-term services and supports (LTSS) today? State adoption of six LTSS options. Kaiser Family Foundation. 2013. Available from: https://www.kff.org/medicaid/issue-brief/how-is-the-affordable-care-act-leading-to-changes-in-medicaid-long-term-services-and-supports-ltss-today-state-adoption-of-six-ltss-options/.
18 Reaves EL, Musumeci M. Medicaid and long-term services and supports: A primer. Kaiser Family Foundation. 2015. Available from: https://www.kff.org/medicaid/report/medicaid-and-long-term-services-and-supports-a-primer/.
19 Scully D, Cho EG, Hall JM, Walter K, Walls J, Fox-Grage W, Ujvari K. At the crossroads: Providing long-term services and supports at a time of high demand and fiscal constraint. AARP Public Policy Institute. 2013. Available from: https://www.aarp.org/content/dam/aarp/research/public_policy_institute/health/2013/crossroads-ltss-in-brief-AARP-ppi-health.pdf.
20 Murray C, Tourtellotte A, Lipson D, Wysocki A. Medicaid long term services and supports annual expenditures report: Federal fiscal years 2017 and 2018. Chicago, IL: Mathematica. 2021.
21 Congressional Budget Office. Rising demand for long-term services and supports for elderly people. 2013. Available from: https://www.cbo.gov/sites/default/files/cbofiles/attachments/44363-LTC.pdf.
22 Kaye HS, Harrington C, LaPlante MP. Long-term care: Who gets it, who provides it, who pays, and how much? Health Aff (Millwood) 29(1):11–21. 2010.20048355
23 Freedman VA, Spillman BC. Disability and care needs among older Americans. Milbank Q 92(3):509–41. 2014.25199898
24 Favreault M, Dey J. Long-term services and supports for older Americans: Risks and financing research brief. 2016. Available from: https://aspe.hhs.gov/basic-report/long-term-services-and-supports-older-americans-risks-and-financing-research-brief.
25 White HK. Post-acute care: Current state and future directions. J Am Med Dir Assoc 20(4):392–5. 2019. Available from: https://www.jamda.com/action/showPdf?pii=S1525-8610%2819%2930262-2.30954131
26 Centers for Medicare & Medicaid Services. 412.29: Classification criteria for payment under the inpatient rehabilitation facility prospective payment system. Available from: https://www.govinfo.gov/content/pkg/CFR-2011-title42-vol2/pdf/CFR-2011-title42-vol2-sec412-29.pdf.
27 American Hospital Association. Fact sheet: Inpatient rehabilitation facilities—A unique and critical service. 2019. Available from: https://www.aha.org/system/files/media/file/2019/07/fact-sheet-irf-0719.pdf.
28 Buczko W, Kennell and Associates, RTI International. Determining medical necessity and appropriateness of care for Medicare long term care hospitals. Baltimore, MD: Centers for Medicare & Medicaid Services. 2011. Available from: https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/Reports/Research-Reports-Items/CMS1247454.
29 Gage B, Morley M, Smith L, Ingber MJ, Deutsch A, Kline T, et al. Post-acute care payment reform demonstration: Final report. Baltimore, MD: Centers for Medicare & Medicaid Services. 2012. Available from: https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/Reports/Research-Reports-Items/PAC_Payment_Reform_Demo_Final.
30 Johnson RW, Toohey D, Wiener JM. Meeting the long-term care needs of the baby boomers: How changing families will affect paid helpers and institutions. 2007. Available from: https://www.urban.org/research/publication/meeting-long-term-care-needs-baby-boomers.
31 Kaye HS. Disability rates for working-age adults and for the elderly have stabilized, but trends for each mean different results for costs. Health Aff (Millwood) 32(1):127–34. 2013.23297280
32 Stone RI. Chapter 22: Emerging issues in long-term care. In: Binstock RH, George L, Cutler S, Hendricks J, Schulz J (editors). Handbook of aging and the social sciences. 6th ed. Waltham, MA: Academic Press, 397–418. 2006.
33 The Lewin Group. Medicaid and long-term care: New challenges, new opportunities, and implications for a comprehensive national long-term care strategy. 2010. Available from: https://www.lewin.com/content/dam/Lewin/Resources/Site_Sections/Publications/GenworthMedicaidandLTCFinalReport62310.pdf.
34 Decker FH. Nursing homes, 1977–99: What has changed, what has not? Hyattsville, MD: National Center for Health Statistics. 2005. Available from: https://www.cdc.gov/nchs/data/nnhsd/nursinghomes1977_99.pdf.
35 Doty P. The evolving balance of formal and informal, institutional and non-institutional long-term care for older Americans: A thirty-year perspective. Public Policy Aging Rep 20(1):3–9. 2010.
36 Doty P. Private pay home care: New models of access and service delivery. Public Policy Aging Rep 27(3):111–20. 2017.
37 Wiener JM. After CLASS: The Long-Term Care Commission’s search for a solution. Health Aff (Millwood) 32(5):831–4. 2013.23650314
38 White House Conference on Aging Staff. Long-term services and supports policy brief. 2015. Available from: https://archive.whitehouseconferenceonaging.gov/home/blog/policy/post/long-term-services-and-supports.html.
39 Institute of Medicine. Retooling for an aging America: Building the health care workforce. Washington, DC: National Academies Press. 2008. Available from: https://www.nationalacademies.org/hmd/reports/2008/retooling-for-an-aging-america-building-the-health-care-workforce.aspx.
40 U.S. Department of Health and Human Services. The supply and demand of professional social workers providing long-term care services: Report to Congress. 2006. Available from: https://aspe.hhs.gov/daltcp/reports/2006/SWsupply.htm.
41 Spetz J, Trupin L, Bates T, Coffman JM. Future demand for long-term care workers will be influenced by demographic and utilization changes. Health Aff (Millwood) 34(6):936–45. 2015.26056198
42 Alzheimer’s Association. 2013 Alzheimer’s disease facts and figures. Alzheimers dement 9(2):208–45. 2013.23507120
43 Alzheimer’s Association. 2018 Alzheimer’s disease facts and figures. Alzheimers dement 14(3):367–429. 2018.
44 Office of Inspector General. Medicare hospices: Certification and Centers for Medicare & Medicaid Services oversight. 2007. Available from: https://oig.hhs.gov/oei/reports/oei-06-05-00260.pdf.
45 Wiener JM, Lux L, Johnson R, Greene AM. National Survey of Residential Care Facilities: Sample frame construction and benchmarking report. 2010. Available from: https://aspe.hhs.gov/reports/national-survey-residential-care-facilities-sample-frame-construction-benchmarking-report-0.
46 Moss AJ, Harris-Kojetin LD, Sengupta M, Park-Lee E, Caffrey C, Rosenoff E, et al. Design and operation of the 2010 National Survey of Residential Care Facilities. National Center for Health Statistics. Vital Health Stat 1(54). 2011. Available from: https://www.cdc.gov/nchs/data/series/sr_01/sr01_054.pdf.
47 Medicare Payment Advisory Commission (MedPAC). March 2019 report to the Congress: Medicare payment policy. Washington, DC: MedPAC. Available from: https://www.medpac.gov/document/march-2019-report-to-the-congress-medicare-payment-policy.
48 Centers for Medicare & Medicaid Services. Home Health Services data archive, 2018 annual files: Home Health Compare Access database download, vwPRVDR table (archived 10/04/2018). 2018. Available from: https://data.cms.gov/provider-data/archived-data/home-health-services.
49 Centers for Medicare & Medicaid Services. Hospice care data archive, 2018 annual files: Hospice Compare - General Information table (archived 11/04/2018). Available from: https://data.cms.gov/provider-data/archived-data/hospice-care.
50 Centers for Medicare & Medicaid Services. Nursing homes including rehab services data archive, 2018 annual files: ProviderInfo_Download table (archived 10/13/2018). Available from: https://data.cms.gov/provider-data/archived-data/nursing-homes.
51 Centers for Medicare & Medicaid Services. Staffing data submission Payroll Based Journal (PBJ). Available from: https://www.cms.gov/Medicare/Quality-Initiatives-Patient-Assessment-Instruments/NursingHomeQualityInits/Staffing-Data-Submission-PBJ.html.
52 Geng F, Stevenson DG, Grabowski DC. Daily nursing home staffing levels highly variable, often below CMS expectations. Health Aff (Millwood) 38(7):1095–100.
53 Centers for Medicare & Medicaid Services. Inpatient rehabilitation facilities data archive, 2018 annual files: Inpatient Rehab Facility - General Information table (archived 9/4/2018). Available from: https://data.cms.gov/provider-data/archived-data/inpatient-rehabilitation-facilities.
54 Centers for Medicare & Medicaid Services. Long-term care hospitals data archive, 2018 annual files: Long-Term Care Hospital - General Information table (archived 9/4/2018). Available from: https://data.cms.gov/provider-data/archived-data/long-term-care-hospitals.
55 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. National Center for Health Statistics. Vital Health Stat 2(175). 2017. Available from: https://www.cdc.gov/nchs/data/series/sr_02/sr02_175.pdf.
56 RTI International. SUDAAN user’s manual (Release 11.0.0) [computer software]. 2012.
57 StataCorp LP. Stata statistical software (Stata/SE) (Release 12.1) [computer software]. 2013.