# Appendix III. Supporting Tables

Table IX

Post-acute and long-term care services providers, by geographical and organizational characteristics and sector: United States, 2017–2018

Characteristic | Adult day services center | SE | Home health agency | SE | Hospice | SE | Inpatient rehabilitation facility | SE | Long-term care hospital | SE | Nursing home | SE | Residential care community | SE
| Number
Number of providers^1^ | 4,200 | 12 | 11,500 | … | 4,700 | … | 1,200 | … | 400 | … | 15,600 | … | 31,400 | 300
Number of beds or licensed maximum capacity^1^ | 283,200 | 8,500 | … | … | … | … | 344,600 | 9,700 | 26,500 | 1,500 | 1,655,400 | 7,600 | 1,183,600 | 43,000
Average number of beds or licensed maximum capacity^2,3^ | 68 | 2 | --- | --- | --- | --- | 298 | 8 | 68 | 4 | 106 | 0 | 38 | 1
Average number of people served^3,4^
Daily | 65 | 2 | … | … | … | … | --- | --- | --- | --- | 85 | 0 | 32 | 1
Annually | … | … | 458 | 11 | 356 | 11 | 348 | 10 | 293 | 11 | … | … | … | …
Number of people served^5^ | Percent distribution
Category 1 | 22.9 | 1.5 | 42.7 | 0.5 | 37.1 | 0.7 | 15.0 | 1.1 | 9.1 | 1.5 | 5.5 | 0.2 | 62.9 | 1.3
Category 2 | 58.7 | 1.8 | 24.4 | 0.4 | 32.5 | 0.7 | 46.2 | 1.5 | 58.3 | 2.5 | 65.4 | 0.4 | 31.2 | 1.5
Category 3 | 18.5 | 1.4 | 32.9 | 0.5 | 30.3 | 0.7 | 38.8 | 1.5 | 32.6 | 2.4 | 29.1 | 0.4 | 6.0 | 0.8
Region
Northeast | 19.3 | 0.1 | 9.1 | 0.3 | 9.3 | 0.4 | 15.2 | 1.1 | 11.0 | 1.6 | 16.6 | 0.3 | 7.4 | 0.2
Midwest | 15.5 | 0.1 | 26.8 | 0.4 | 20.3 | 0.6 | 24.8 | 1.3 | 22.0 | 2.1 | 33.0 | 0.4 | 26.6 | 0.7
South | 33.3 | 0.1 | 43.9 | 0.5 | 37.4 | 0.7 | 41.3 | 1.5 | 54.6 | 2.5 | 34.9 | 0.4 | 25.8 | 0.3
West | 32.0 | 0.1 | 20.3 | 0.4 | 32.9 | 0.7 | 18.7 | 1.2 | 13.3 | 1.7 | 15.5 | 0.3 | 40.2 | 0.4
Metropolitan statistical area status
Metropolitan | 84.6 | 1.4 | 85.4 | 0.3 | 81.1 | 0.6 | 86.7 | 1.0 | 94.8 | 1.2 | 71.9 | 0.4 | 86.5 | 1.7
Micropolitan | 11.1 | 1.2 | 8.1 | 0.3 | 11.5 | 0.5 | 11.5 | 1.0 | 4.6 | 1.1 | 13.5 | 0.3 | 8.7 | 1.5
Neither | 4.3 | 0.8 | 6.5 | 0.2 | 7.4 | 0.4 | 1.8 | 0.4 | 0.5 | 0.4 | 14.6 | 0.3 | 4.9 | 1.1
Ownership
For profit | 42.3 | 1.8 | 82.0 | 0.4 | 66.4 | 0.7 | 34.4 | 1.4 | 67.2 | 2.4 | 70.0 | 0.4 | 79.2 | 1.9
Nonprofit | 52.8 | 1.8 | 14.3 | 0.3 | 21.3 | 0.6 | 46.9 | 1.5 | 23.1 | 2.1 | 23.2 | 0.3 | 18.8 | 1.8
Government and other | 4.8 | 0.8 | 3.7 | 0.2 | 12.3 | 0.5 | 18.7 | 1.2 | 9.8 | 1.5 | 6.8 | 0.2 | 2.0 | 0.8
Certification | Percent
Medicare certified | … | … | 98.6 | 0.1 | --- | --- | 100.0 | … | 100.0 | … | 97.8 | 0.1 | … | …
Medicaid certified | 74.9 | 1.5 | 78.9 | 0.4 | --- | --- | 95.9 | 0.6 | 76.9 | 2.1 | 95.4 | 0.2 | 46.9 | 2.8
Chain affiliated | 42.7 | 1.8 | --- | --- | --- | --- | --- | --- | --- | --- | 58.6 | 0.4 | 60.3 | 2.8

… Category not applicable.--- Data not available.

^1^Estimates are rounded as whole numbers to the nearest hundred.

^2^For adult day services centers (ADSCs), capacity is based on licensed maximum capacity. For nursing homes (NHs), residential care communities (RCCs), inpatient rehabilitation facilities (IRFs), and long-term care hospitals (LTCHs), capacity is based on number of licensed or certified beds.

^3^Averages are based on unrounded numbers.

^4^Estimated number of ADSC participants represents current participants in 2018. Estimated number of home health agency (HHA) and IRF patients represents patients discharged in 2017. Estimated number of hospice (HOS) and LTCH patients represents patients who received care at any time in 2017. Estimated number of NH and RCC residents represents current residents in 2018.

^5^For ADSCs, NHs, and RCCs, number of people served is based on current users on any given day in 2018, and the categories are 1–25, 26–100, and 101 or more. For HHAs, HOSs, IRFs, and LTCHs, number of people served is based on number of patients in 2017, and the categories are 1–100, 101–300, and 301 or more.

NOTES: SE is standard error. Percent distributions may not add to 100 because of rounding. Percentages are based on unrounded estimates.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Table X

Staffing characteristics of post-acute and long-term care services providers, by staff type and sector: United States, 2018

Characteristic | Adult day services center | SE | Home health agency | SE | Hospice | SE | Inpatient rehabilitation facility | SE | Long-term care hospital | SE | Nursing home | SE | Residential care community | SE
| Number
Total number of nursing and social work employee FTEs | 24,300 | 1,089 | 139,200 | 1,530 | 91,300 | 1,620 | 263,900 | 7,000 | 13,600 | 440 | 660,000 | 4,780 | 474,200 | 31,300
Nursing and social work employee FTEs | Percent distribution
Registered nurse | 26.6 | 1.4 | 51.5 | 0.4 | 48.4 | 0.3 | 92.4 | 0.3 | 79.9 | 1.7 | 12.1 | 0.1 | 14.7 | 2.3
Licensed practical nurse or licensed vocational nurse | 8.6 | 0.5 | 21.3 | 0.3 | 8.7 | 0.2 | 8.6 | 0.3 | 17.9 | 1.7 | 23.3 | 0.1 | 14.1 | 1.3
Aide | 55.6 | 1.5 | 24.7 | 0.4 | 31.6 | 0.3 | --- | --- | --- | --- | 62.8 | 0.1 | 70.0 | 2.2
Social worker | 9.3 | 0.6 | 2.6 | 0.0 | 11.3 | 0.1 | --- | --- | --- | --- | 1.8 | 0.0 | 1.2 | 0.2
Providers with one or more employee FTEs | Percent
Registered nurse | 61.0 | 1.7 | 99.6 | 0.1 | †100.0 | ... | 97.6 | 0.5 | 96.9 | 0.9 | 71.4 | 0.4 | 41.9 | 2.6
Licensed practical nurse or licensed vocational nurse | 41.4 | 1.8 | 72.8 | 0.4 | 65.1 | 0.7 | 87.3 | 1.0 | 76.2 | 2.2 | 70.9 | 0.4 | 41.3 | 2.3
Aide | 65.2 | 1.7 | 89.5 | 0.3 | 97.8 | 0.2 | --- | --- | --- | --- | 70.8 | 0.4 | 73.5 | 2.6
Social worker | 37.1 | 1.8 | 46.7 | 0.5 | 99.2 | 0.1 | --- | --- | --- | --- | 55.7 | 0.4 | 13.0 | 1.8
Activities director or staff | 80.5 | 1.5 | --- | --- | --- | --- | --- | --- | --- | --- | 69.7 | 0.4 | 56.7 | 2.6
Employee hours per resident or participant per day | Mean
Registered nurse | 0.31 | 0.04 | --- | --- | --- | --- | --- | --- | --- | --- | 0.37 | 0.01 | 0.74 | 0.29
Licensed practical nurse or licensed vocational nurse | 0.15 | 0.03 | --- | --- | --- | --- | --- | --- | --- | --- | 0.61 | 0.01 | 0.43 | 0.18
Aide | 0.74 | 0.09 | --- | --- | --- | --- | --- | --- | --- | --- | 1.67 | 0.01 | 2.28 | 0.29
Social worker | 0.08 | 0.01 | --- | --- | --- | --- | --- | --- | --- | --- | 0.06 | 0.00 | 0.06 | 0.03
Activities director or staff | 0.63 | 0.07 | --- | --- | --- | --- | --- | --- | --- | --- | 0.14 | 0.00 | 0.39 | 0.11

--- Data not available.

† Percentage is 90% or higher but estimate is not displayed as it may pose a disclosure risk.

… Category not applicable.

NOTES: SE is standard error. FTE is full-time equivalent. Percent distributions may not add to 100 because of rounding. Percentages are based on unrounded estimates.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Table XI

Services provided by post-acute and long-term care services providers, by type of service and sector: United States, 2018

Service provided | Adult day services center | SE | Home health agency | SE | Hospice | SE | Inpatient rehabilitation facility | SE | Long-term care hospital | SE | Nursing home | SE | Residential care community | SE
| Percent
Social work | 50.2 | 1.9 | 81.7 | 0.4 | 100.0 | – | 97.5 | 0.5 | 88.2 | 1.6 | 63.8 | 0.4 | 62.8 | 2.9
Mental health or counseling | 37.7 | 1.8 | --- | --- | 97.3 | 0.2 | --- | --- | --- | --- | 63.6 | 0.4 | 62.0 | 2.7
Therapeutic | 45.4 | 1.8 | 95.8 | 0.2 | 97.9 | 0.2 | 99.8 | 0.1 | 99.5 | 0.4 | 71.7 | 0.4 | 71.7 | 2.6
Skilled nursing or nursing | 62.0 | 1.7 | 100.0 | – | 100.0 | – | --- | --- | --- | --- | 71.6 | 0.4 | 70.8 | 2.6
Pharmacy or pharmacist services | 30.9 | 1.7 | 4.5 | 0.2 | --- | --- | 99.0 | 0.3 | 98.0 | 0.7 | 70.1 | 0.4 | 84.5 | 2.2
Hospice | 12.6 | 1.2 | 5.4 | 0.2 | … | … | --- | --- | --- | --- | 83.0 | 0.3 | 66.8 | 2.9
Dietary and nutritional | 60.5 | 1.8 | --- | --- | --- | --- | 98.8 | 0.3 | 96.4 | 0.9 | 71.5 | 0.4 | 82.6 | 2.2
Dementia-specific units
Only serve residents with dementia | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | 0.3 | 0.1 | 6.0 | 1.3
Have a distinct unit, wing, or floor designated for dementia special care | --- | --- | --- | --- | --- | --- | --- | --- | --- | --- | 13.4 | 0.3 | 19.4 | 1.6

– Quantity zero.

--- Data not available.

… Category not applicable.

NOTES: SE is standard error. Percent distributions may not add to 100 due to rounding. Percentages are based on unrounded estimates.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Table XII

Post-acute and long-term care users, by selected characteristics and sector: United States, 2017–2018

Characteristic^1^ | Adult day services center | SE | Home health agency | SE | Hospice | SE | Inpatient rehabilitation facility | SE | Long-term care hospital | SE | Nursing home | SE | Residential care community | SE
| Number
Users^2^ | 251,100 | 7,080 | 4,940,270 | --- | 1,562,524 | 47,679 | 380,430 | 10,956 | 115,822 | 4,448 | 1,321,200 | 6,640 | 918,700 | 33,620
Age | Percent distribution
Under 65 | 39.4 | 2.1 | 17.3 | 0.0 | 5.2 | 0.1 | 12.1 | 0.2 | 25.7 | 0.5 | 16.9 | 0.0 | 7.5 | 1.2
65 and over | 60.6 | 2.1 | 82.7 | 0.0 | 94.8 | 0.1 | 87.9 | 0.2 | 74.3 | 0.5 | 83.1 | 0.0 | 92.5 | 1.3
65–74 | 17.8 | 1.4 | 27.5 | 0.0 | 17.6 | 0.1 | 31.9 | 0.2 | 34.3 | 0.3 | 19.5 | 0.0 | 12.1 | 1.6
75–84 | 24.1 | 1.7 | 29.9 | 0.0 | 29.2 | 0.1 | 33.5 | 0.1 | 26.5 | 0.2 | 27.2 | 0.0 | 25.5 | 2.4
85 and over | 18.6 | 1.5 | 25.2 | 0.0 | 48.0 | 0.2 | 22.5 | 0.3 | 13.5 | 0.5 | 36.4 | 0.0 | 54.9 | 2.6
Sex
Men | 43.5 | 1.9 | 39.4 | 0.1 | 41.6 | 0.1 | 45.8 | 0.2 | 51.8 | 0.3 | 36.7 | 0.0 | 32.6 | 2.1
Women | 56.5 | 1.9 | 60.6 | 0.1 | 58.4 | 0.1 | 54.2 | 0.2 | 48.2 | 0.3 | 63.3 | 0.0 | 67.4 | 2.1
Race and ethnicity
Hispanic | 22.2 | 1.9 | 7.0 | 0.2 | 6.5 | 0.4 | 5.8 | 0.4 | 9.7 | 0.9 | 5.7 | 0.0 | 1.9 | 0.6
Non-Hispanic White | 44.8 | 2.1 | 76.8 | 0.3 | 82.3 | 0.5 | 79.9 | 0.6 | 66.3 | 1.1 | 73.9 | 0.0 | 89.4 | 1.8
Non-Hispanic Black | 16.8 | 1.4 | 12.1 | 0.2 | 8.3 | 0.2 | 10.8 | 0.4 | 19.8 | 0.9 | 14.9 | 0.0 | 5.9 | 1.4
Other^3^ | 16.3 | 1.9 | 4.1 | 0.1 | 3.0 | 0.2 | 3.5 | 0.2 | 4.1 | 0.3 | 5.5 | 0.0 | 2.8 | 0.9
Medicaid payer source | 72.3 | 1.9 | 9.1 | 0.0 | --- | --- | --- | --- | --- | --- | 62.0 | 0.2 | 18.1 | 2.3
Diagnosis^4^ | Percent
Alzheimer disease or other dementias | 27.8 | 1.8 | 35.5 | 0.2 | 46.3 | 0.3 | 35.6 | 0.4 | 45.5 | 0.7 | 49.1 | 0.0 | 33.7 | 2.8
Arthritis | 18.5 | 1.6 | 61.7 | 0.2 | 29.6 | 0.2 | 62.8 | 0.3 | 52.6 | 0.6 | 27.6 | 0.0 | 20.5 | 2.1
Asthma | 5.6 | 0.9 | 11.8 | 0.1 | 3.7 | 0.0 | 12.0 | 0.1 | 13.9 | 0.2 | --- | --- | 2.0 | 0.5
Chronic kidney disease | 5.7 | 0.9 | 54.7 | 0.1 | 39.2 | 0.2 | 61.2 | 0.3 | 81.4 | 0.5 | --- | --- | 6.5 | 1.1
Chronic obstructive pulmonary disease | 6.8 | 0.9 | 32.0 | 0.2 | 20.1 | 0.2 | 33.1 | 0.3 | 55.4 | 0.8 | --- | --- | 10.6 | 1.9
Depression | 21.8 | 1.7 | 40.5 | 0.1 | 23.7 | 0.2 | 49.2 | 0.4 | 51.8 | 0.5 | 48.8 | 0.0 | 27.5 | 2.5
Diabetes | 29.7 | 1.7 | 45.2 | 0.2 | 26.6 | 0.2 | 48.2 | 0.3 | 64.2 | 0.6 | 34.8 | 0.0 | 20.4 | 2.3
Heart disease^5^ | 13.3 | 1.4 | 54.4 | 0.2 | 37.9 | 0.3 | 59.8 | 0.4 | 68.3 | 0.6 | 20.1 | 0.0 | 17.3 | 1.9
High blood pressure or hypertension | 51.1 | 2.0 | 89.2 | 0.1 | 50.3 | 0.3 | 93.6 | 0.1 | 93.5 | 0.3 | 76.9 | 0.0 | 55.2 | 2.7
Osteoporosis | 12.7 | 1.6 | 15.0 | 0.1 | 6.4 | 0.1 | 17.4 | 0.2 | 10.5 | 0.2 | 11.4 | 0.0 | 12.0 | 1.5
Need assistance in physical functioning
Bathing | 74.8 | 1.9 | 98.3 | 0.0 | --- | --- | 99.7 | 0.0 | --- | --- | 96.5 | 0.1 | 77.3 | 2.2
Dressing | 64.2 | 2.0 | 95.6 | 0.0 | --- | --- | 99.9 | 0.0 | --- | --- | 92.7 | 0.1 | 61.7 | 2.5
Toileting | 52.7 | 2.1 | 90.2 | 0.0 | --- | --- | 99.4 | 0.0 | --- | --- | 89.8 | 0.1 | 48.7 | 2.9
Walking or locomotion | 57.7 | 2.0 | 97.2 | 0.0 | --- | --- | 99.8 | 0.0 | --- | --- | 92.4 | 0.1 | 69.0 | 2.6
Transferring in and out of a chair or bed | 53.6 | 2.1 | 95.4 | 0.0 | --- | --- | 99.9 | 0.0 | --- | --- | 87.3 | 0.1 | 51.0 | 2.8
Eating | 41.4 | 2.0 | 66.8 | 0.0 | --- | --- | 83.9 | 0.1 | --- | --- | 60.2 | 0.3 | 26.3 | 2.5
Adverse event | Percent
Overnight hospital stay^6^ | 5.4 | 0.8 | 15.0 | 0.0 | --- | --- | --- | --- | --- | --- | 14.6 | 0.0 | 7.7 | 1.1
Emergency department visit | 9.7 | 1.0 | 16.1 | 0.0 | --- | --- | --- | --- | --- | --- | --- | --- | 12.1 | 1.5
Fall | 14.4 | 1.3 | --- | --- | --- | --- | --- | --- | --- | --- | 17.0 | 0.0 | 29.6 | 2.4

--- Data not available.

0.0 Quantity more than zero but less than 0.05.

^1^All cases with missing data were removed from the denominator when calculating percentages. For variables that had missing data for more than 10% of all cases, the percentage missing is reported in a footnote.

^2^Estimates are rounded as whole numbers to the nearest hundred. Estimated number of adult day services center (ADSC) participants, nursing home (NH) residents, and residential care community (RCC) residents represents current users in 2018. Estimated number of home health agency (HHA) and inpatient rehabilitation facility (IRF) patients represents patients discharged in 2017. Estimated number of hospice (HOS) and long-term care hospital (LTCH) patients represents patients who received care at any time in 2017.

^3^For ADSCs and RCCs, includes non-Hispanic American Indian or Alaska Native (AIAN), non-Hispanic Asian, non-Hispanic Native Hawaiian or Other Pacific Islander (NHOPI), non-Hispanic of two or more races, and unknown race and ethnicity. For HOS, HHAs, NHs, IRFs, and LTCHs, other race includes non-Hispanic AIAN, non-Hispanic Asian, and non-Hispanic NHOPI.

^4^For ADSCs, the percentage of missing data was 11.2% for Alzheimer disease, 14.3% for arthritis, 14.8% for asthma, 15.0% for chronic kidney disease, 15.3% for chronic obstructive pulmonary disease (COPD), 13.1% for depression, 11.8% for diabetes, 14.1% for heart disease, 13.1% for hypertension, and 15.8% for osteoporosis. For RCCs, the percentage missing was 14.1% for arthritis, 15.6% for asthma, 15.3% for chronic kidney disease, 13.6% for COPD, 12.6% for depression, 12.5% for diabetes, 13.0% for heart disease, 11.5% for hypertension, and 15.0% for osteoporosis.

^5^For ADSC participants and RCC residents, heart disease includes congestive heart failure, coronary or ischemic heart disease, heart attack, and stroke. For HHA, HOS, IRF, and LTCH patients, heart disease refers to ischemic heart disease. For NH residents, heart disease refers to coronary artery disease, congestive heart failure, and stroke.

^6^For NH residents, overnight hospital stay is defined as any resident in the 2018 Minimum Data Set Active Resident Episode Table 3rd quarter file having any inpatient hospital stay as determined in the 2018 Medicare Provider Analysis and Review data file.

NOTES: SE is standard error. Percent distributions may not add to 100 due to rounding. Percentages are based on unrounded estimates.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Table XIII

Nursing home residents, by selected characteristics and length of stay: United States, 2018

Characteristic | Short stay (fewer than 100 days)^1^ | SE | Long stay (100 days or more)^1^ | SE
| Number
Users^2^ | 598,712 | 580 | 773,765 | 580
Age | Percent distribution
Under 65 | 18.9 | 0.1 | 15.4 | 0.0
65 and over | 81.1 | 0.1 | 84.6 | 0.0
65–74 | 21.8 | 0.1 | 17.7 | 0.0
75–84 | 28.7 | 0.1 | 26.1 | 0.1
85 and over | 30.7 | 0.1 | 40.9 | 0.1
Sex
Men | 41.0 | 0.1 | 33.4 | 0.1
Women | 59.0 | 0.1 | 66.6 | 0.1
Race and ethnicity
Hispanic | 5.6 | 0.0 | 5.7 | 0.0
Non-Hispanic White | 73.3 | 0.1 | 74.4 | 0.1
Non-Hispanic Black | 14.6 | 0.1 | 15.2 | 0.0
Other^3^ | 6.5 | 0.0 | 4.7 | 0.0
Medicaid payer source | --- | --- | --- | ---
Diagnosis | Percent
Alzheimer disease or other dementias | 35.8 | 0.1 | 57.6 | 0.1
Arthritis | 24.9 | 0.1 | 29.8 | 0.1
Depression | 42.8 | 0.1 | 52.7 | 0.1
Diabetes | 38.1 | 0.1 | 32.7 | 0.1
Heart disease^4^ | 44.7 | 0.1 | 39.8 | 0.1
High blood pressure or hypertension | 77.4 | 0.1 | 76.6 | 0.1
Osteoporosis | 8.8 | 0.0 | 13.0 | 0.0
Need assistance in physical functioning
Bathing | --- | --- | --- | ---
Dressing | --- | --- | --- | ---
Toileting | --- | --- | --- | ---
Walking or locomotion | --- | --- | --- | ---
Transferring in and out of a chair or bed | --- | --- | --- | ---
Eating | --- | --- | --- | ---
Adverse events
Overnight hospital stay^5^ | 23.0 | 0.1 | 8.15 | 0.03
Emergency department visit | --- | --- | --- | ---
Fall | 13.5 | 0.1 | 19.3 | 0.0

0.0 Quantity more than zero but less than 0.05.--- Data not available.

^1^Average length of stay among all residents is 485 days; 43% of residents are short-stay and 57% are long-stay.

^2^Estimates are rounded as whole numbers to the nearest hundred. Estimated number of nursing home residents represents current residents in 2018.

^3^Includes non-Hispanic American Indian or Alaska Native, non-Hispanic Asian, and non-Hispanic Native Hawaiian or Other Pacific Islander.

^4^Includes coronary artery disease, congestive heart failure, and stroke.

^5^Defined as any resident in the 2018 Minimum Data Set Active Resident Episode Table 3rd quarter file having any inpatient hospital stay as determined in the 2018 Medicare Provider Analysis and Review data file.

NOTES: SE is standard error. Percent distributions may not add to 100 because of rounding. Percentages are based on unrounded estimates.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.