# Appendix II. Crosswalk of Definitions by Sector

Table III

Geographic and organizational characteristics, by sector

Characteristic | Definition | Survey data | | Administrative data
Characteristic | Definition | Adult day services center (ADSC) | Residential care community (RCC) | Home health agency (HHA) | Hospice (HOS) | Inpatient rehabilitation facility (IRF) | Long-term care hospital (LTCH) | Nursing home (NH)
Number of providers^1^ | Number of paid, regulated long-term and post-acute care services providers | Number of ADSCs based on 2018 National Study of Long-Term Care Providers (NSLTCP) | Number of assisted living and similar RCCs based on 2018 NSLTCP | Number of HHAs certified to provide services under Medicare, Medicaid, or both in third quarter 2018 | Number of hospices certified to provide services under Medicare, Medicaid, or both in third quarter 2018 | Number of IRFs certified to provide services under Medicare, Medicaid, or both in third quarter 2018 | Number of LTCHs certified to provide services under Medicare, Medicaid, or both in third quarter 2018 | Number of NHs certified to provide services under Medicare, Medicaid, or both in third quarter 2018
Region | Grouping of states into geographic areas corresponding to groups used by the U.S. Census Bureau | Four census regions1 = Northeast2 = Midwest3 = South4 = West | Four census regions1 = Northeast2 = Midwest3 = South4 = West | Derived from: [STATE_CD]1 = Northeast2 = Midwest3 = South4 = West | Derived from: [STATE_CD]1 = Northeast2 = Midwest3 = South4 = West | Derived from: [STATE_CD]1 = Northeast2 = Midwest3 = South4 = West | Derived from: [STATE_CD]1 = Northeast2 = Midwest3 = South4 = West | Derived from: [STATE_CD]1 = Northeast2 = Midwest3 = South4 = West
Metropolitan statistical area (MSA) and micropolitan statistical area | Geographic entities defined by 2013 Office of Management and Budget standards for delineating MSAsA metropolitan area contains a core urban area of 50,000 or more population, and a micropolitan area contains an urban core of at least 10,000 (but less than 50,000) population. | Metropolitan statistical area status1 = Metropolitan2 = Micropolitan3 = Neither | Metropolitan statistical area status1 = Metropolitan2 = Micropolitan3 = Neither | Derived from: [ZIP_CD]1 = Metropolitan2 = Micropolitan3 = Neither | Derived from: [ZIP_CD]1 = Metropolitan2 = Micropolitan3 = Neither | Derived from: [ZIP_CD]1 = Metropolitan2 = Micropolitan3 = Neither | Derived from: [ZIP_CD]1 = Metropolitan2 = Micropolitan3 = Neither | Derived from: [ZIP_CD]1 = Metropolitan2 = Micropolitan3 = Neither
Capacity^2^ | The number of beds or spaces available to the community | Q2. What is the maximum number of participants allowed at this adult day services center at this location?This may be called the allowable daily capacity and is usually determined by law or by fire code, but may also be a program decision. | Q2. At this residential care community, what is the number of licensed, registered, or certified residential care beds? Include both occupied and unoccupied beds. | … | … | Derived from: [CRTFD_ BED_CNT]Number of beds in Medicare- or Medicaid-certified areas within a facility | Derived from: [CRTFD_ BED_CNT]Number of beds in Medicare- or Medicaid-certified areas within a facility | Derived from: [CRTFD_ BED_CNT]Number of beds in Medicare- or Medicaid-certified areas within a facility
Ownership | Classified into three categories: for profit, nonprofit, and government and other | 1 = For profit2 = Nonprofit3 = Government and other Derived from: [OWNERSHP]Q3.What is the type of ownership of this adult day services center? 1 = Private, nonprofit 2 = Private, for profit3 = Publicly traded company or limited liability company (LLC)4 = Government—federal, state, county, localIf OWNERSHP = 1, then OWN = 2; if OWNERSHP = 2 or 3, then OWN = 1; if OWNERSHP = 4, then OWN = 3. | 1 = For profit2 = Nonprofit3 = Government and other Derived from: [OWNERSHP]Q3.What is the type of ownership of this adult day services center? 1 = Private, nonprofit 2 = Private, for profit3 = Publicly traded company or limited liability company (LLC)4 = Government—federal, state, county, localIf OWNERSHP = 1, then OWN = 2; if OWNERSHP = 2 or 3, then OWN = 1; if OWNERSHP = 4, then OWN = 3. | 1 = For profit2 = Nonprofit3 = Government and otherDerived from: [GNRL_CNTL_TYPE_CD]01 = Voluntary NP, religious affiliation02 = Voluntary NP, private 03 = Voluntary NP, other 04 = Proprietary05 = Government, state or county06 = Government, combination government and voluntary07 = Government, localIf GNRL_CNTL_TYPE_CD = ‘01’, ‘02’, or ‘03’, then OWN = 2; if GNRL_CNTL_TYPE_CD = ‘04’, then OWN = 1; if GNRL_CNTL_TYPE_ CD = ‘05’, ‘06’, or ‘07’, then OWN = 3. | 1 = For profit2 = Nonprofit3 = Government and otherDerived from: [GNRL_CNTL_TYPE_CD]01 = Nonprofit, church02 = Nonprofit, private03 = Nonprofit, other04 = Proprietary, individual05 = Proprietary, partnership06 = Proprietary, corporation07 = Proprietary, other08 = Government, state09 = Government, county10 = Government, city11 = Government, city or county12 = Combination government and NP 13 = OtherIf GNRL_CNTL_TYPE_CD = ‘01’, ‘02’, or ‘03’, then OWN= 2; if GNRL_CNTL_TYPE_CD = ‘04’, ‘05’, ‘06’, or ‘07’, then OWN = 1; if GNRL_CNTL_TYPE_CD = ‘08’, ‘09’, ‘10’, ‘11’, ‘12’, or ‘13’, then OWN = 3. | 1 = For profit2 = Nonprofit3 = Government and otherDerived from: [GNRL_CNTL_TYPE_CD] 01 = Church02 = Private (not for profit)03 = Other04 = Private (for profit)05 = Federal06 = State07 = Local08 = Hospital district or authority09 = Physician ownership If GNRL_CNTL_TYPE_CD = ‘01’ or ‘02’, then OWN = 2; if GNRL_CNTL_TYPE_ CD = ‘04’, then OWN = 1; if GNRL_CNTL_TYPE_CD = ‘03’, ‘05’, ‘06’, ‘07’, ‘08’, ‘09’, or ‘10’, then OWN = 3. | 1 = For profit2 = Nonprofit3 = Government and otherDerived from: [GNRL_CNTL_TYPE_CD] 01 = Church02 = Private (not for profit)03 = Other04 = Private (for profit)05 = Federal or local06 = State07 = Federal or local08 = Hospital district or authority 09 = Physician ownership 10 = Tribal If GNRL_CNTL_TYPE_CD = ‘01’ or ‘02’, then OWN = 2; if GNRL_CNTL_TYPE_ CD = ‘04’, then OWN = 1; if GNRL_CNTL_TYPE_CD = ‘03’, ‘05’, ‘06’, ‘07’, ‘08’, ‘09’, or ‘10’, then OWN = 3. | 1 = For profit2 = Nonprofit3 = Government and otherDerived from: [GNRL_CNTL_TYPE_CD]01 = For profit, individual02 = For profit, partnership03 = For profit, corporation04 = Nonprofit, church related05 = Nonprofit, corporation06 = Nonprofit, other07 = Government, state08 = Government, county09 = Government, city10 = Government, city or county11 = Government, hospital district12 = Government, federal13 = Limited liability companyIf GNRL_CNTL_TYPE _CD = ‘01’, ‘02’, ‘03’, or ‘13’, then OWN = 1; if GNRL_CNTL_TYPE_CD = ‘04’, ‘05’, or ‘06’, then OWN = 2; if GNRL_CNTL_TYPE_CD = ‘07’, ‘08’, ‘09’, ‘10’, ‘11’, or ‘12’, then OWN = 3.
Number of people served categories | Three categories based on the number of current participants or residents in 2018 or the number of patients that received or ended care at any time in calendar year 2017 | 1 = 1–252 = 26–1003 = 101 or moreDerived from: [TOTPART] | 1 = 1–252 = 26–1003 = 101 or moreDerived from: [TOTRES]Q17. What is the total number of residents currently living at this residential care community?Please include residents for whom a bed is being held while in the hospital. If you have respite care residents, please include them. | 1 = 1–1002 = 101–3003 = 301 or moreDerived from: [TOTPAT from OBQI]Number of home health patients discharged at any time in calendar year (CY) 2017, regardless of payment source | 1 = 1–1002 = 101–3003 = 301 or moreDerived from: [BENE_CNT in IPBS data]Number of patients with a Medicare claim for provider at any time in CY 2017 | 1 = 1–1002 = 101–3003 = 301 or moreDerived from: [BENE_CNT in IPBS data]Number of patients with a Medicare claim for provider at any time in CY 2017 | 1 = 1–1002 = 101–3003 = 301 or moreDerived from: [BENE_CNT in IPBS data]Number of patients with a Medicare claim for provider at any time in CY 2017 | 1 = 1–252 = 26–1003 = 101 or moreDerived from: [CNSUS_RSDNT_CNT]Number of current residents reported in Certification and Survey Provider Enhanced Reports (CASPER), defined as those in certified beds regardless of payer source
Medicare certification | Medicare certification | … | … | 1 = Certified2 = Not certifiedDerived from: [PGM_ PRTCPTN_CD]Indicates if the provider participates in Medicare, Medicaid, or both programs 1 = Medicare only2 = Medicaid only3 = Medicare and Medicaid If PGM_PRTCPTN_CD = 1 or 3, then MEDICARE = 1. | 1 = Certified2 = Not certifiedAll hospices included in CASPER are assumed to be Medicare-certified. | 1 = Certified2 = Not certifiedDerived from: [PGM_ PRTCPTN_CD]Indicates if the provider participates in Medicare, Medicaid, or both programs1 = Medicare only2 = Medicaid only3 = Medicare and Medicaid If PGM_PRTCPTN_CD = 1 or 3, then MEDICARE = 1. | 1 = Certified2 = Not certifiedDerived from: [PGM_ PRTCPTN_CD]Indicates if the provider participates in Medicare, Medicaid, or both programs1 = Medicare only2 = Medicaid only3 = Medicare and Medicaid If PGM_PRTCPTN_CD = 1 or 3, then MEDICARE = 1. | 1 = Certified2 = Not certifiedDerived from: [PGM_ PRTCPTN_CD]Indicates if the provider participates in Medicare, Medicaid, or both programs 1 = Medicare only2 = Medicaid only3 = Medicare and Medicaid If PGM_PRTCPTN_CD = 1 or 3, then MEDICARE = 1.
Medicaid certification | Medicaid certification or participation status | 1 = Certified2 = Not certifiedDerived from: [MEDICAID][SCREENER] Is this adult day services center authorized or otherwise set up to participate in Medicaid (Medicaid state plan, Medicaid waiver, or Medicaid managed care) or part of a Program of All-Inclusive Care for the Elderly (PACE)? | 1 = Certified2 = Not certifiedDerived from: [MEDICAID]Q6. Is this residential care community authorized or otherwise set up to participate in Medicaid? | 1 = Certified2 = Not certifiedDerived from: [PGM_ PRTCPTN_CD]Indicates if the provider participates in Medicare, Medicaid, or both programs1 = Medicare only2 = Medicaid only3 = Medicare and MedicaidIf PGM_PRTCPTN_CD = 2 or 3, then MEDICAID = 1. | --- | 1 = Certified2 = Not certifiedDerived from: [PGM_ PRTCPTN_CD]Indicates if the provider participates in Medicare, Medicaid, or both programs1 = Medicare only2 = Medicaid only3 = Medicare and MedicaidIf PGM_PRTCPTN_CD = 2 or 3, then MEDICAID = 1. | 1 = Certified2 = Not certifiedDerived from: [PGM_ PRTCPTN_CD]Indicates if the provider participates in Medicare, Medicaid, or both programs1 = Medicare only2 = Medicaid only3 = Medicare and MedicaidIf PGM_PRTCPTN_CD = 2 or 3, then MEDICAID = 1. | 1 = Certified2 = Not certifiedDerived from: [PGM_ PRTCPTN_CD]Indicates if the provider participates in Medicare, Medicaid, or both programs 1 = Medicare only2 = Medicaid only3 = Medicare and MedicaidIf PGM_PRTCPTN_CD = 2 or 3, then MEDICAID = 1.
Chain affiliation | Chain affiliation status | 1 = Yes2 = No Q4. Is this center owned by a person, group, or organization that owns or manages two or more adult day services centers? This may include a corporate chain. | 1 = Yes 2 = No Q4. Is this residential care community owned by a person, group, or organization that owns or manages two or more residential care communities? This may include a corporate chain. | --- | --- | --- | --- | 1 = Yes2 = No Derived from: [MLT_ OWND_FAC_ORG_SW]Owned or leased by multifacility organizationCheck “yes” if the facility is owned or leased by a multifacility organization, otherwise check “no.” A multifacility organization is an organization that owns two or more long-term care facilities. The owner may be an individual or a corporation. Leasing of facilities by corporate chains is included in this definition.

… Category not applicable.--- Data not available.

^1^Study-specific eligibility criteria were used to define RCCs. See Appendix I for information on eligibility criteria.

^2^For NH, the number of certified beds was used because current residents in Certification and Survey Provider Enhanced Reports (CASPER) are defined as those in certified beds regardless of payer source.

NOTES: For survey data (ADSC and RCC), question numbers refer to the NSLTCP provider questionnaires. Questionnaires and detailed documentation on survey variables are available from: https://www.cdc.gov/nchs/npals/questionnaires.htm. For HHA, HOS, NH, IRF, and LTCH, when the data source is not specified, the source is Centers for Medicare and Medicaid Services CASPER data.

SOURCES: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018, and Centers for Medicare and Medicaid Services, 2017 and 2018.

Table IV

Staffing: Nursing, social work, and activities employees, by sector

Characteristic | Definition | Survey data | | Administrative data
Characteristic | Definition | Adult day services center (ADSC) | Residential care community (RCC) | Home health agency (HHA) | Hospice (HOS) | Inpatient rehabilitation facility (IRF) | Long-term care hospital (LTCH) | Nursing home (NH)
Registered nurse^1^ | Number of full-time equivalent (FTE) registered nurse (RN) employees (based on a 35-hour workweek) | Derived RNFTE1 from: [RNFT1, RNPT1]Q28b. RNs: number of full-time employees; number of part-time employees | Derived RNFTE1 from: [RNFT1, RNPT1]Q31b. RNs: number of full-time employees; number of part-time employees | Derived RNFTE1 from: [RN_CNT]Number of FTE registered professional nurses employed by a provider | Derived RNFTE1 from: [RN_CNT]Number of FTE registered professional nurses employed by a provider | Derived RNFTE1 from: [RN_CNT]Number of FTE registered professional nurses employed by a provider | Derived RNFTE1 from: [RN_CNT]Number of FTE registered professional nurses employed by a provider | Derived RNFTE1 from: [RN_FLTM_CNT, RN_PRTM_ CNT]Number of FTE registered nurses employed by a facility on a full-time basis; number of FTE registered nurses employed by a facility on a part-time basis
Licensed practical nurse (LPN) or licensed vocational nurse (LVN)^1^ | Number of FTE licensed practical nurse or licensed vocational nurse (LPN/LVN) employees (based on a 35-hour workweek) | Derived LPNFTE1 from: [LPNFT1, LPNPT1]Q28c. LPNs/LVNs: number of full-time employees; number of part-time employees | Derived LPNFTE1 from: [LPNFT1, LPNPT1] Q31c. LPNs/LVNs: number of full-time employees; number of part-time employees | Derived LPNFTE1 from: [LPN_LVN_CNT]Number of FTE licensed practical or vocational nurses employed by a provider | Derived LPNFTE1 from: [LPN_LVN_CNT]Number of FTE licensed practical or vocational nurses employed by a provider | Derived LPNFTE1 from: [LPN_LVN_CNT]Number of FTE licensed practical or vocational nurses employed by a provider | Derived LPNFTE1 from: [LPN_LVN_CNT]Number of FTE licensed practical or vocational nurses employed by a provider | Derived LPNFTE1 from: [LPN_LVN_FLTM_CNT, LPN_ LVN_PRTM_CNT]Number of FTE licensed practical or vocational nurses employed by a facility on a full-time basis; part-time basis
Aide^1^ | Number of FTE aide employees (based on a 35-hour workweek)Aides refer to paid staff providing direct care and assistance to residents, participants, or patients with a broad range of activities. | Derived AIDEFTE1 from: [AIDEFT1, AIDEPT1]Q28d. Certified nursing assistants, nursing assistants, home health aides, home care aides, personal care aides, personal care assistants, and medication technicians or medication aides: number of full-time employees; number of part-time employees | Derived AIDEFTE1 from: [AIDEFT1, AIDEPT1]Q31d. Certified nursing assistants, nursing assistants, home health aides, home care aides, personal care aides, personal care assistants, and medication technicians or medication aides: number of full-time employees; number of part-time employees | Derived AIDEFTE1 from: [HH_AIDE_CNT]Number of FTE home health aides employed by a provider | Derived AIDEFTE1 from: [HH_AIDE_EMPLEE_CNT]Number of FTE home health aides employed by a provider | --- | --- | Derived AIDFTE1 from: [NRS_AIDE_FLTM_CNT, NRS_AIDE_PRTM_CNT, MDCTN_AIDE_FLTM_CNT, MDCTN_AIDE_PRTM_CNT]Number of FTE certified nurse aides employed by a facility on a full-time basis; part-time basisNumber of FTE medication aides or technicians employed by a facility on a full-time basis; part-time basis
Social worker^1^ | Number of FTE social worker employees (based on a 35-hour workweek) | Derived SOCWFTE1 from: [SOCWFT1, SOCWPT1]Q28e. Social workers—licensed social workers or persons with a bachelor’s or master’s degree in social work: number of full-time employees; number of part-time employees | Derived SOCWFTE1 from: [SOCWFT1, SOCWPT1]Q31e. Social workers—licensed social workers or persons with a bachelor’s or master’s degree in social work: number of full-time employees; number of part-time employees | Derived SOCWFTE1 from: [SCL_WORKR_CNT]Number of FTE social workers employed by a provider | Derived SOCWFTE1 from: [MDCL_SCL_WORKR_CNT]Number of FTE social workers employed by a provider | --- | --- | Derived SOCWFTE1 from: [SCL_WORKR_FLTM_CNT, SCL_WORKR_PRTM_CNT]Number of FTE social workers employed by a facility on a full-time basis; part-time basis
Activities directors or activities staff^1^ | Number of FTE activities directors or activities staff employees (based on a 35-hour workweek) | Derived ACTFTE1 from: [ACTFT1, ACTPT1]Q28f. Activities directors or activities staff: number of full-time employees; number of part-time employees | Derived ACTFTE1 from: [ACTFT1, ACTPT1]Q31f. Activities directors or activities staff: number of full-time employees; number of part-time employees | --- | --- | --- | --- | Derived ACTFTE1 from: [ACTVTY_PROFNL_FLTM_CNT, ACTVTY_PROFNL_PRTM_CNT, ACTVTY_STF_OTHR_FLTM_CNT, ACTVTY_STF_OTHR_PRTM_CNT)Number of FTE activity professionals employed full-time by a facility; employed part-time by a facility; number of FTE other activities staff providing therapeutic services employed full-time by a facility; part-time basis
Hours per resident or participant per day (HPRD or HPPD)^2^ | Number of hours providing care for one resident or participant per day for a given staff typeFor ADSCs, HPPD was computed by multiplying the number of FTEs by 35 hours, and dividing the total number of hours by the number of current enrolled participants and by 5 days. For RCCs, NHs, IRFs, and LTCHs, HPRD was computed by multiplying the number of FTEs by 35 hours and dividing by the number of current residents in the facility, and by 7 days. | Derived from: [RNFTE1, LPNFTE1, AIDEFTE1, SOCWFTE1, ACTFTE1 / TOTPART]RNHPPD1 = (RNFTE1 * 35) / TOTPART / 5 days; LPNHPPD1 = (LPNFTE1 * 35) / TOTPART / 5 days; AIDEHPPD1 = (AIDEFTE1 * 35) / TOTPART / 5 days; SOCWHPPD1 = (SOCWFTE1 * 35) / TOTPART / 5 days; ACTHPPD1 = (ACTFTE1 * 35) / TOTPART / 5 days | Derived from: [RNFTE1, LPNFTE1, AIDEFTE1, SOCWFTE1, ACTFTE1 / TOTRES]RNHPRD1 = (RNFTE1 * 35) / TOTRES / 7 days; LPNHPRD1 = (LPNFTE1 * 35) / TOTRES / 7 days; AIDEHPRD1 = (AIDEFTE1 * 35) / TOTRES / 7 days; SOCWHPRD1 = (SOCWFTE1 * 35) / TOTRES / 7 days; ACTHPRD1 = (ACTFTE1 * 35) / TOTRES / 7 days | --- | --- | Derived from RNFTE and LPNFTERNHPRD1 = RNFTE1 * 35 / BENE_CNT / 7 days LPNHPRD1 = (LPNFTE1 * 35) / BENE_CNT / 7 days | Derived from RNFTE and LPNFTERNHPRD1 = RNFTE1 * 35 / BENE_CNT / 7 days LPNHPRD1 = (LPNFTE1 * 35) / BENE_CNT / 7 days | Derived from: [RNFTE, LPNFTE, AIDEFTE, SOCWFTE / CNSUS_ RSDNT_ CNT]RNHPRD1 = (RNFTE1 * 35) / CNSUS_RSDNT_CNT / 7 days; LPNHPRD1 = (LPNFTE1 * 35) / CNSUS_RSDNT_CNT / 7 days; AIDEHPRD1 = AIDEFTE1 * 35) / CNSUS_RSDNT_CNT / 7 days; SOCWHPRD1 = (SOCWFTE1 * 35) / CNSUS_RSDNT_CNT / 7 days; ACTHPRD1 = (ACTFTE1 * 35) / CNSUS_RSDNT_CNT / 7 days

--- Data not available.

^1^For ADSC and RCC, the number of full-time and part-time employees for a given staff type were converted into FTEs with an assumption that full time is 1.0 FTE and part time is 0.5 FTE. For HHA and HOS, the number of FTE employees by staff type is provided in data. For NH, data report the number of hours for a given staff type during the 2 weeks before their annual survey. CMS converts the number of hours into FTEs (based on a 35-hour workweek). For all provider types, outliers are defined as cases with FTEs that are two standard deviations above or below the mean for a given size category and recoded as the size-specific mean FTE for the given staff type. See Appendix I for more information on editing of the staffing data.

^2^Residential settings (as in, RCC and NH) and ADSCs operate and staff differently to serve the needs of their residents or participants; these differences between provider types are reflected in using total participants and 5 days (as opposed to current residents and 7 days when computing HPRD.

NOTES: For survey data (ADSC and RCC), question numbers refer to the National Study of Long-Term Care Providers (NSLTCP) provider questionnaires. Questionnaires and detailed documentation on survey variables are available from: https://www.cdc.gov/nchs/npals/questionnaires.htm. For HHA, HOS, NH, IRF, and LTCH, when the data source is not specified, the source is Centers for Medicare and Medicaid Services Certification and Survey Provider Enhanced Reports (CASPER) data.

SOURCES: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018, and Centers for Medicare and Medicaid Services, 2017 and 2018.

Table V

Services provided by post-acute and long-term care services providers, by sector

Characteristic | Definition | Survey data | | Administrative data
Characteristic | Definition | Adult day services center (ADSC) | Residential care community (RCC) | Home health agency (HHA) | Hospice (HOS) | Inpatient rehabilitation facility (IRF) | Long-term care hospital (LTCH) | Nursing home (NH)
Social work services^1^ | In survey data, refers to services provided by licensed social workers or persons with a bachelor’s or master’s degree in social work, and may include an array of services such as psychosocial assessment, individual or group counseling, and referral servicesIn administrative data, refers to qualified social workers services in nursing homes, and medical social services in home health agencies and hospices | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVSOCW1, SERVSOCW2, SERVSOCW3, SERVSOCW4]Q23c. Social work services—provided by licensed social workers or persons with a bachelor’s or master’s degree in social work, and may include an array of services such as psychosocial assessment, individual or group counseling, and referral services1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVSOCW1, SERVSOCW2, SERVSOCW3, SERVSOCW4]Q26c. Social work services—provided by licensed social workers or persons with a bachelor’s or master’s degree in social work, and may include an array of services such as psychosocial assessment, individual or group counseling, and referral services1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not providedDerived from: [MDCL_SCL_ SRVC_CD]Indicates how medical social services are provided:0 = Not provided1 = Provided by staff2 = Provided under arrangement3 = CombinationIf MCDL_SCL_SRVC_CD = 0, then SERVSOCW = 2; if MDCL_SCL_SRVC_CD > 0, then SERVSOCW = 1. | 1 = Provided2 = Not providedDerived from: [MDCL_SCL_ SRVC_CD]Indicates how medical social services are provided:0 = Not provided1 = Provided by staff2 = Provided under arrangement3 = CombinationIf MCDL_SCL_SRVC_CD = 0, then SERVSOCW = 2; if MDCL_SCL_SRVC_CD > 0, then SERVSOCW = 1. | 1 = Provided2 = Not providedDerived from: [SCL_SRVC_CD]Services: Social CD 1) Not provided 2) Provided by staff 3) Provided by staff and under arrangement 4)Provided under arrangement If SCL_SRVC_ CD = 1, then SERVSOCW = 2; if SCL_SRVC_ CD = 2, 3, or 4, then SERVSOCW = 1. | 1 = Provided 2 = Not providedDerived from: [SCL_SRVC_CD]Services: Social CD1) Not provided2) Provided by staff3) Provided by staff and under arrangement 4) Provided under arrangement If SCL_SRVC_ CD = 1, then SERVSOCW = 2; if SCL_SRVC_CD = 2, 3, or 4, then SERVSOCW = 1. | 1 = Provided2 = Not providedDerived from: [SCL_WORK_SRVC_ONST_RSDNT_SW, SCL_WORK_SRVC_ONST_NRSDNT_SW, SCL_WORK_SRVC_OFSITE_RSDNT_SW]Qualified social workers services:1) Services provided onsite to residents, either by employees or contractors;2) Services provided onsite to non-residents;3) Services provided to residents offsite or not routinely provided onsiteIf “no” to 1, 2, and 3, then SERVSOCW = 2; if “yes” to any, then SERVSOCW = 1.
Mental health or counseling services^1^ | In survey data, refers to services that target a person’s mental, emotional, psychological, or psychiatric well-being, and may include diagnosing, describing, evaluating, and treating mental conditions. For hospices, counseling services are provided to the patient and family to assist them in “minimizing the stress and problems that arise from the terminal illness, related conditions, and the dying process” (https://www.cms.gov/ Regulations-and-Guidance/ Guidance/Manuals/ downloads/som107ap_m_ hospice.pdf). | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVMH1, SERVMH2, SERVMH3, SERVMH4]Q23d. Mental health services— target participants’ mental, emotional, psychological, or psychiatric well-being and may include diagnosing, describing, evaluating, and treating mental conditions1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVMH1, SERVMH2, SERVMH3, SERVMH4]Q26d. Mental health services—target residents’ mental, emotional, psychological, or psychiatric well-being and may include diagnosing, describing, evaluating, and treating mental conditions1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | --- | 1 = Provided2 = Not providedDerived from: [CNSLNG_ SRVC_CD]Counseling services 0 = Not provided1 = Provided by agency staff2 = Provided under arrangement3 = CombinationIf CNSLNG_SRVC_CD = 0, then SERVMH = 2; if CNSLNG_SRVC_CD > 0, then SERVMH = 1. | --- | --- | 1 = Provided2 = Not providedDerived from: [MENTL_HLTH_ONST_RSDNT_SW, MENTL_HLTH_ONST_NRSDNT_SW, MENTL_HLTH_OFSITE_RSDNT_SW]Mental health services1) Services provided onsite to residents, either by employees or contractors;2) Services provided onsite to non-residents;3) Services provided to residents offsite or not routinely provided onsiteIf “no” to 1), 2), and 3), SERVMH = 2; if “yes” to any, then SERVMH = 1.
Therapeutic services^1^ | Refers to providing any of the three therapeutic services: physical therapy, occupational therapy, or speech therapy or pathology. | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVTX1, SERVTX2, SERVTX3, SERVTX4]Q23e. Any therapeutic services—physical, occupational, or speech1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVTX1, SERVTX2, SERVTX3, SERVTX4]Q26e. Any therapeutic services—physical, occupational, or speech1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not providedDerived from: [PT_SRVC_CD, OT_ SRVC_CD, SPCH_ THRPY_ SRVC_CD]Physical therapy, occupational therapy, or speech therapy0 = Not provided1 = Provided by agency staff 2 = Provided under arrangement3 = CombinationIf PT_SRVC_CD = 0 AND OT_SRVC_CD = 0 and SPCH_THRPY_SRVC_CD = 0, SERVTX = 2; else SERVTX = 1. | 1 = Provided2 = Not providedDerived from: [PT_SRVC_CD, OT_SRVC_CD, SPCH_ PTHLGY_SRVC_CD]Physical therapy, occupational therapy, or speech pathology0 = Not provided1 = Provided by agency staff 2 = Provided under arrangement3 = CombinationIf PT_SRVC_CD = 0 and OT_SRVC_CD = 0 and SPCH_PTHLGY_SRVC_CD = 0, SERVTX = 2; else SERVTX = 1. | 1 = Provided2 = Not providedDerived from: [PT_SRVC_CD, OT_SRVC_CD, SPCH_PTHLGY_SRVC_CD]1) Not provided2) Provided by staff3) Provided by staff and under arrangement 4) Provided under arrangementIf PT_SRVC_CD = 1 and OT_SRVC_CD = 1 and SPCH_PTHLGY_SRVC_CD = 1, then SERVTX = 2; if any 2, 3, or 4, then SERVTX = 1. | 1 = Provided 2 = Not providedDerived from: [PT_SRVC_CD, OT_SRVC_CD, SPCH_PTHLGY_SRVC_CD]1) Not provided 2) Provided by staff3) Provided by staff and under arrangement 4) Provided under arrangement If PT_SRVC_CD = 1 and OT_SRVC_CD = 1 and SPCH_PTHLGY_SRVC_CD = 1, then SERVTX = 2; if any 2, 3, or 4, then SERVTX = 1. | 1 = Provided2 = Not providedDerived from: [PT_ONST_RSDNT_SW, PT_ONST_NRSDNT_SW, PT_OFSITE_RSDNT_SW, OT_SRVC_ONST_RSDNT_SW, OT_SRVC_ONST_NRSDNT_SW, OT_SRVC_OFSITE_RSDNT_SW, SPCH_PTHLGY_ONST_RSDNT_SW, SPCH_PTHLGY_ONST_NRSDNT_SW, SPCH_PTHLGY_OFSITE_RSDNT_SW]Physical therapist services, occupational therapist services, or speech or language pathologists1) Services provided onsite to residents, either by employees or contractors;2) Services provided onsite to non-residents;3) Services provided to residents offsite or not routinely provided onsiteIf “no” to all nine variables, then SERVTX = 2; if “yes” to any, then SERVTX = 1.
Pharmacy services^1^ | Refers to services including filling of or delivery of prescriptions | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVRX1, SERVRX2, SERVRX3, SERVRX4]Q23f. Pharmacy services—including filling of or delivery of prescriptions1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVRX1, SERVRX2, SERVRX3, SERVRX4]Q26f. Pharmacy services—including filling of or delivery of prescriptions1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not providedDerived from: [PHRMCY_ SRVC_CD]Pharmaceutical services 0 = Not provided1 = Provided by agency staff2 = Provided under arrangement3 = CombinationIf PHRMCY_SRVC_CD = 0, then SERVRX_RC = 2; if PHRMCY_SRVC_CD > 0, then SERVRX = 1. | --- | 1 = Provided2 = Not providedDerived from: [PHRMCY_SRVC_CD] Services: Pharmacy code1) Not provided 2) Provided by staff 3) Provided by staff and under arrangement 4) Provided under arrangementIf PHRMCY_SRVC_CD = 1, then SERVRX = 2; if PHRMCY_SRVC_CD = 2, 3, or 4, then SERVRX = 1. | 1 = Provided2 = Not providedDerived from: [PHRMCY_SRVC_CD] Services: Pharmacy code 1) Not provided 2) Provided by staff 3) Provided by staff and under arrangement 4) Provided under arrangement If PHRMCY_SRVC_CD = 1, then SERVRX = 2; if PHRMCY_SRVC_CD = 2, 3, or 4, then SERVRX = 1. | 1 = Provided2 = Not providedDerived from: [PHRMCY_SRVC_ONST_RSDNT_SW, PHRMCY_SRVC_ONST_NRSDNT_SW, PHRMCY_SRVC_ OFSITE_RSDNT_SW]Pharmacist services1) Services provided onsite to residents, either by employees or contractors;2) Services provided onsite to non-residents;3) Services provided to residents offsite or not routinely provided onsiteIf “no” to 1, 2, and 3, SERVRX = 2; if “yes” to any, then SERVRX = 1.
Skilled nursing services^1^ | For home health agencies, the definition for nursing services is not provided in CMS’ “State Operations Manual”For hospices, nursing services are “routinely available on a 24-hour basis, 7 days a week,” and hospices must “provide nursing care and services by or under the supervision of a registered nurse” (available from: https://www.cms. gov/Regulations-and- Guidance/Guidance/ Manuals/downloads/ som107ap_m_hospice.pdf)Nursing services in nursing homes refer to “coordination, implementation, monitoring and management of resident care plans. Includes provision of personal care services, monitoring resident responsiveness to environment, range-of-motion exercises, application of sterile dressings, skin care, naso-gastric tubes, intravenous fluids, catheterization, administration of medications, etc.” (CMS form 671) | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVNURS1, SERVNURS2, SERVNURS3, SERVNURS4]Q23i. Skilled nursing services— must be performed by an RN or LPN and are medical in nature1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVNURS1, SERVNURS2, SERVNURS3, SERVNURS4]Q26i. Skilled nursing services— must be performed by an RN or LPN and are medical in nature1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not providedDerived from: [NRSNG_SRVC_CD]Nursing care0 = Not provided1 = Provided by agency staff 2 = Provided under arrangement3 = CombinationIf NURSNG_SRVC_CD = 0, then SERVNURS = 2; if NURSNG_SRVC_CD > 0 then, SERVNURS = 1. | 1 = Provided2 = Not providedDerived from: [NRSNG_SRVC_CD]Nursing services 0 = Not provided1 = Provided by agency staff2 = Provided under arrangement3 = CombinationIf NURSNG_SRVC_CD = 0, then SERVNURS = 2; if NURSNG_SRVC_CD > 0 then, SERVNURS = 1. | --- | --- | 1 = Provided2 = Not providedDerived from: [NRSNG_SRVC_ONST_RSDNT_SW, NRSNG_SRVC_ONST_NRSDNT_SW, NRSNG_SRVC_OFSITE_RSDNT_SW]Nursing services1) Services provided onsite to residents, either by employees or contractors;2) Services provided onsite to non-residents;3) Services provided to residents offsite or not routinely provided onsiteIf ”no” to 1, 2, and 3, then SERVNURS = 2; if “yes” to any, then SERVNURS = 1.
Hospice services^1^ | For home health agencies, the agency was coded as providing hospice services if the agency also participates in the Medicare program as a hospice. If nursing homes have at least one bed identified and dedicated for residents needing hospice services or have one or more residents receiving hospice care benefits, they were coded as providing hospice services. | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVHOS1, SERVHOS2, SERVHOS3, SERVHOS4]Q23b. Hospice services1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVHOS1, SERVHOS2, SERVHOS3, SERVHOS4]Q26b. Hospice services1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not providedDerived from: [MDCR_ HOSPC_SW]Indicates if the agency also participates in the Medicare program as a hospice providerIf MDCR_HOSPC_SW = ‘Y’, then, SERVHOS = 1; if MDCR_HOSPC_SW = ‘N’, then SERVHOS = 2. | … | --- | --- | 1 = Provided2 = Not providedDerived from: [HOSPC_BED_CNT, CNSUS_HOSPC_CARE_CNT]1) Number of beds in a unit identified and dedicated by a facility for residents needing hospice services2) Number of residents receiving hospice care benefitIf HOSPC_BED_CNT > 0 or CNSUS_HOSPC_CARE_CNT > 0, then SERVHOS = 1; if HOSPC_BED_CNT = 0 and CNSUS_HOSPC_CARE_CNT = 0, then SERVHOS = 2.
Dietary and nutritional services^1^ | Refers to dietary and nutritional services | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVDIET1, SERVDIET2, SERVDIET3, SERVDIET4]Q23h. Dietary and nutritional services1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | 1 = Provided2 = Not provided (includes referral only)Derived from: [SERVDIET1, SERVDIET2, SERVDIET3, SERVDIET4]Q26h. Dietary and nutritional services1 = Provides the service by paid center employees2 = Arranges for the service to be provided by outside service providers3 = Refers participants or family to outside service providers4 = Does not provide, arrange, or refer for this service | --- | --- | 1 = Provided 2 = Not providedDerived from: [DTRY_SRVC_CD] Services: Dietary code1) Not provided2) Provided by staff3) Provided by staff and under arrangement4) Provided under arrangement If DTRY_SRVC_CD = 1, then SERVDIET = 2; if DTRY_SRVC_CD = 2, 3, or 4, then SERVDIET = 1. | 1 = Provided2 = Not providedDerived from: [DTRY_SRVC_CD] Services: Dietary code1) Not provided 2) Provided by staff 3) Provided by staff and under arrangement 4) Provided under arrangement If DTRY_SRVC_CD = 1, then SERVDIET = 2; if DTRY_SRVC_CD = 2, 3, or 4, then SERVDIET = 1. | 1 = Provided2 = Not providedDerived from: [DTRY_ONST_RSDNT_SW, DTRY_ONST_NRSDNT_SW, DTRY_OFSITE_RSDNT_SW]Dietary services1) Services provided onsite to residents, either by employees or contractors;2) Services provided onsite to non-residents;3) Services provided to residents offsite or not routinely provided onsiteIf ”no” to 1, 2, and 3, then SERVDIET = 2; if “yes” to any, then SERVDIET = 1.
Dementia care units | Refers to the provision of dementia care units or only serving residents with dementia in residential care communitiesIn nursing homes, refers to having any certified Alzheimer’s bed and only serving residents with dementia if Alzheimer’s beds equals total certified beds | --- | 1 = Serves only residents with dementia2 = Provides dementia care units within larger communityDerived from: [ONLYDEM, DEMWING]Q7. Does this residential care community only serve adults with dementia or Alzheimer’s disease?Q8. [If no to Q7] Does this residential care community have a distinct unit, wing, or floor that is designated as a dementia or Alzheimer’s care unit? | --- | --- | --- | --- | 1 = Serves only residents with dementia2 = Provides dementia care units within larger facilityDerived from: [CRTFD_BED_CNT, ALZHMR_BED_CNT]Number of certified beds; number of beds in a unit identified and dedicated by the facility for residents with Alzheimer’s diseaseIf CRTFD_BED_CNT = ALZHMR_BED_CNT, then DSU = 1; if ALZHMR_BED_CNT > 0, then DSU = 2; else DSU = 0.

--- Data not available.… Category not applicable.

^1^For ADSC and RCC, the questionnaires used “mark all that apply” questions to ask about different services provided. Respondents indicated as many as three different ways that the ADSC or RCC provided a given service. For each service, four binary variables were derived: three variables corresponding to three different ways that ADSCs or RCCs provided the service (for example, by paid employees, by arranging for service to be provided by outside providers, or by referral); and one variable indicating whether the ADSC or RCC provided the service in any of these ways or did not provide the service. For this report, a derived variable with two mutually exclusive categories was used: 1) provided by paid employees, or arranging for service to be provided by outside providers, in addition to referral; 2) not provided or provided only by referral.

NOTES: For survey data (ADSC and RCC), question numbers refer to the National Study of Long-Term Care Providers (NSLTCP) provider questionnaires. Questionnaires and detailed documentation on survey variables are available from: https://www.cdc.gov/nchs/npals/questionnaires.htm. For administrative data (HHA, HOS, NH, IRF, and LTCH), when the data source is not specified, the source is Centers for Medicare and Medicaid Services Certification and Survey Provider Enhanced Reports (CASPER) data.

SOURCES: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018, and Centers for Medicare and Medicaid Services, 2017 and 2018.

Table VI

Use of post-acute and long-term care services, by sector

Characteristic | Definition | Survey data | | Administrative data
Characteristic | Definition | Adult day services center (ADSC) | Residential care community (RCC) | Home health agency (HHA) | Hospice (HOS) | Inpatient rehabilitation facility (IRF) | Long-term care hospital (LTCH) | Nursing home (NH)
Number of services users | Number of users of services provided by paid, regulated long-term care services providers | Q3. What is the total number of participants currently enrolled at this adult day services center at this location? This number was also used to create categories of number of people served (SIZE). | Q5. What is the total number of residents currently living at this residential care community? Please include residents for whom a bed is being held while in the hospital. If you have respite care residents, please include them. This number was also used to create categories of number of people served (SIZE). | Derived from: [OBQI]Number of home health patients whose episode of care ended at any time in CY (calendar year) 2017 (i.e., discharges), regardless of payment sourceThis number was also used to create categories of number of people served (SIZE). | Derived from: [BENE_CNT from Institutional Provider and Beneficiary Summary (IPBS) data]Number of patients for whom a Medicare claim was submitted at any time in CY 2017BENE_CNT was also used to create categories of number of people served (SIZE) and used as the denominator when computing percentages for all aggregate patient-level measures. | Derived from: [BENE_CNT from IPBS data]Number of patients for whom a Medicare claim was submitted at any time in CY 2017BENE_CNT was also used to create categories of number of people served (SIZE) and used as the denominator when computing percentages for all aggregate resident-level measures. | Derived from: [BENE_CNT from IPBS data]Number of patients for whom a Medicare claim was submitted at any time in CY 2017BENE_CNT was also used to create categories of number of people served (SIZE) and used as the denominator when computing percentages for all aggregate resident-level measures. | Number of current residents in certified beds in Certification and Survey Provider Enhanced Reports (CASPER) nursing home dataCNSUS_RSDNT_CNT was also used to create categories of number of people served (SIZE) and used as the denominator when computing percentages for all aggregate resident-level measures.
Age | Number of services users under age 65 | Derived from: What is [sampled person’s initials] age in years? AGE < 65 Missing data for AGE were imputed. | Derived from: What is [sampled person’s initials] age in years?AGE < 65 Missing data for AGE were imputed. | Derived from: [MSR_201_ VAL from OBQI]Calculated age at the time of episode of care | Derived from: [AGE_ LESS_65/ BENE_CNT from IPBS]Number of beneficiaries under age 65 utilizing the provider | Derived from: [AGE_ LESS_65 / BENE_CNT from IPBS]Number of beneficiaries under age 65 utilizing the provider | Derived from: [AGE_ LESS_65 / BENE_CNT from IPBS]Number of beneficiaries under age 65 utilizing the provider | Derived from: [C_RSDNT_AGE_NUM from MARET data]Calculated age at the time of nursing home assessment
Age | Number of services users between ages 65 and 74 | Derived from: What is [sampled person’s initials] age in years?AGE >= 65 and < 75Missing data for AGE were imputed. | Derived from: What is [sampled person’s initials] age in years?AGE >= 65 and < 75Missing data for AGE were imputed. | Derived from: [MSR_201_VAL from OBQI]Calculated age at the time of episode of care | Derived from: [AGE_65_69, AGE_70_74 / BENE_CNT from IPBS data]Number of beneficiaries between ages 65 and 69 utilizing the provider; number of beneficiaries between ages 70 and 74 utilizing the provider | Derived from: [AGE_65_69, AGE_70_74 / BENE_CNT from IPBS data]Number of beneficiaries between ages 65 and 69 utilizing the provider; number of beneficiaries between ages 70 and 74 utilizing the provider | Derived from: [AGE_65_69, AGE_70_74 / BENE_CNT from IPBS data]Number of beneficiaries between ages 65 and 69 utilizing the provider; number of beneficiaries between ages 70 and 74 utilizing the provider | Derived from: [C_RSDNT_AGE_NUM from MARET data]Calculated age at the time of nursing home assessment
Age—Con. | Number of services users between ages 75 and 84 | Derived from: What is [sampled person’s initials] age in years?AGE >= 75 and < 85Missing data for AGE were imputed. | Derived from: What is [sampled person’s initials] age in years?AGE >= 75 and < 85Missing data for AGE were imputed. | Derived from: [MSR_201_VAL from OBQI]Calculated age at the time of episode of care | Derived from: [AGE_75_79, AGE_80_84 / BENE_CNT from IPBS data]Number of beneficiaries between ages 75 and 79 utilizing the provider; number of beneficiaries between ages 80 and 84 utilizing the provider | Derived from: [AGE_75_79, AGE_80_84 / BENE_CNT from IPBS data]Number of beneficiaries between ages 75 and 79 utilizing the provider; number of beneficiaries between ages 80 and 84 utilizing the provider | Derived from: [AGE_75_79, AGE_80_84 / BENE_CNT from IPBS data]Number of beneficiaries between ages 75 and 79 utilizing the provider; number of beneficiaries between ages 80 and 84 utilizing the provider | Derived from: [C_RSDNT_AGE_NUM from MARET data]Calculated age at the time of nursing home assessment
Age—Con. | Number of services users aged 85 and over | Derived from: What is [sampled person’s initials] age in years? AGE >= 85 Missing data for AGE were imputed. | Derived from: What is [sampled person’s initials] age in years? AGE >= 85Missing data for AGE were imputed. | Derived from: [MSR_201_VAL from OBQI]Calculated age at the time of episode of care | Derived from: [AGE_OVER_84 / BENE_CNT from IPBS data]Number of beneficiaries over age 84 utilizing the provider | Derived from: [AGE_OVER_84 / BENE_CNT from IPBS data]Number of beneficiaries over age 84 utilizing the provider | Derived from: [AGE_OVER_84 / BENE_CNT from IPBS data]Number of beneficiaries over age 84 utilizing the provider | Derived from: [C_RSDNT_AGE_NUM from Minimum Data Set Active Resident Episode Table (MARET) data]Calculated age at the time of nursing home assessment
Race and ethnicity | Number of services users of Hispanic or Latino origin | Is [sampled person’s initials] of Hispanic, Latino, or Spanish origin or descent?1 = Yes2 = No3 = Don’t knowMissing data and don’t know for ETHNICITY were imputed. | Is [sampled person’s initials] of Hispanic, Latino, or Spanish origin or descent?1 = Yes2 = No3 = Don’t knowMissing data and don’t know for ETHNICITY were imputed. | Derived from: [RACE_HISPN / BENE_CNT from IPBS data]Number of Hispanic beneficiaries utilizing the provider | Derived from: [RACE_HISPN / BENE_CNT from IPBS data]Number of Hispanic beneficiaries utilizing the provider | Derived from: [RACE_HISPN / BENE_CNT from IPBS data]Number of Hispanic beneficiaries utilizing the provider | Derived from: [RACE_HISPN / BENE_CNT from IPBS data]Number of Hispanic beneficiaries utilizing the provider | Derived from: [A1000D_HSPNC_CD from MARET data]Number of Hispanic residentsCoded so that indicator includes all Hispanic, regardless of race indicator
Race and ethnicity | Number of services users who are non-Hispanic White | Please look at the show card titled “Race” to answer this question. Which one or more of the following would you say is [sampled person’s initials]’s race?5. WhiteCoded so that number includes only non-Hispanic WhiteMissing data for race were imputed. | Please look at the show card titled “Race” to answer this question. Which one or more of the following would you say is [sampled person’s initials]’s race?5. WhiteCoded so that number includes only non-Hispanic WhiteMissing data for race were imputed. | Derived from: [RACE_WHITE / BENE_CNT from IPBS data]Number of non-Hispanic White beneficiaries utilizing the provider | Derived from: [RACE_WHITE / BENE_CNT from IPBS data]Number of non-Hispanic White beneficiaries utilizing the provider | Derived from: [RACE_WHITE / BENE_CNT from IPBS data]Number of non-Hispanic White beneficiaries utilizing the provider | Derived from: [RACE_WHITE / BENE_CNT from IPBS data]Number of non-Hispanic White beneficiaries utilizing the provider | Derived from: [A1000F_WHT_CD from MARET data]Number of White residentsCoded so that indicator includes only non-Hispanic White
Race and ethnicity—Con. | Number of services users who are non-Hispanic Black | Please look at the show card titled “Race” to answer this question. Which one or more of the following would you say is [sampled person’s initials]’s race?3. BlackCoded so that number includes only non-Hispanic BlackMissing data for race were imputed. | Please look at the show card titled “Race” to answer this question. Which one or more of the following would you say is [sampled person’s initials]’s race?3. BlackCoded so that number includes only non-Hispanic BlackMissing data for race were imputed. | Derived from: [RACE_BLACK / BENE_CNT from IPBS data]Number of non-Hispanic Black beneficiaries utilizing the provider | Derived from: [RACE_BLACK / BENE_CNT from IPBS data]Number of non-Hispanic Black beneficiaries utilizing the provider | Derived from: [RACE_BLACK / BENE_CNT from IPBS data]Number of non-Hispanic black beneficiaries utilizing the provider | Derived from: [RACE_BLACK / BENE_CNT from IPBS data]Number of non-Hispanic Black beneficiaries utilizing the provider | Derived from: [A1000C_AFRCN_AMRCN_CD from MARET data]Number of African-American residentsCoded so that indicator includes only non-Hispanic African American
Race and ethnicity—Con. | Number of services users who are of a race other than White or Black | Please look at the show card titled “Race” to answer this question. Which one or more of the following would you say is [sampled person’s initials]’s race?1. American Indian or Alaska Native2. Asian3. Native Hawaiian or Other Pacific IslanderCoded so that number includes only non-Hispanic for each category, multiple race categories selectedMissing data for race were imputed. | Please look at the show card titled “Race” to answer this question. Which one or more of the following would you say is [sampled person’s initials]’s race?1. American Indian or Alaska Native2. Asian3. Native Hawaiian or Other Pacific IslanderCoded so that number includes only non-Hispanic for each category, multiple race categories selectedMissing data for race were imputed. | Derived from: [RACE_NATIND, RACE_API, RACE_OTHER / BENE_CNT from IPBS]Number of American Indian or Alaska Native, Asian or Pacific Islander, and other beneficiaries not elsewhere classified utilizing the provider | Derived from: [RACE_NATIND, RACE_API, RACE_OTHER / BENE_CNT from IPBS]Number of American Indian or Alaska Native, Asian or Pacific Islander, and other beneficiaries not elsewhere classified utilizing the provider | Derived from: [RACE_NATIND, RACE_API, RACE_OTHER / BENE_CNT from IPBS]Number of American Indian or Alaska Native, Asian or Pacific Islander, and other beneficiaries not elsewhere classified utilizing the provider | Derived from: [RACE_NATIND, RACE_API, RACE_OTHER / BENE_CNT from IPBS]Number of American Indian or Alaska Native, Asian or Pacific Islander, and other beneficiaries not elsewhere classified utilizing the provider | Derived from: [A1000A_AMRCN_INDN_AK_NTV_CD, A1000B_ASN_CD, A1000E_NTV_HI_PCFC_ISLNDR_CD from MARET data]Number of American Indian or Alaska Native, Asian, and Native Hawaiian or Pacific Islander residentsCoded so that indicator includes only non-Hispanic “other” races
Sex | Number of services users who are male | What is [sampled person’s initials]’s gender?1. MaleMissing data for sex imputed | What is [sampled person’s initials]’s gender?1. MaleMissing data for sex imputed | Derived from: [MSR_202_VAL from OBQI data]“Patient History, Demographics, Gender: Male” | Derived from: [MALE / BENE_CNT from IPBS data]Number of male beneficiaries utilizing the provider | Derived from: [MALE / BENE_CNT from IPBS data]Number of male beneficiaries utilizing the provider | Derived from: [MALE / BENE_CNT from IPBS data]Number of male beneficiaries utilizing the provider | Derived from: [A0800_GNDR_CD from MARET data]Identifies the resident’s sex:1 = Male
Sex | Number of services users who are female | What is [sampled person’s initials]’s gender?2. FemaleMissing data for sex were imputed. | What is [sampled person’s initials]’s gender? 2. FemaleMissing data for sex were imputed. | Derived from: [MSR_202_VAL from OBQI data]“Patient History, Demographics, Gender: Female” | Derived from: [FEMALE / BENE_CNT from IPBS data]Number of female beneficiaries utilizing the provider | Derived from: [FEMALE / BENE_CNT from IPBS data]Number of female beneficiaries utilizing the provider | Derived from: [FEMALE / BENE_CNT from IPBS data]Number of female beneficiaries utilizing the provider | Derived from: [A0800_GNDR_CD from MARET data]Identifies the resident’s sex:1 = Female
Medicaid as payer source | Number of users with Medicaid paying for any services received | Derived from: TPAYSOURCE: During the last complete month, what was the one primary payment source…1. MEDICAID and MEDPAIDRC and During the last complete month, did Medicaid pay for any of the services that [sampled person’s initials] received at this center? Please include any funding from a Medicaid state plan, Medicaid waiver, Medicaid managed care, or California regional center. 1 = Yes2 = No3 = Don’t knowDon’t know was coded as missing data. | During the last complete month, did Medicaid pay for any of the services that [sampled person’s initials] received at this center? Please include any funding from a Medicaid state plan, Medicaid waiver, Medicaid managed care. 1 = Yes2 = No3 = Don’t knowDon’t know was coded as missing data. | Derived from: [MSR_207_VAL from OBQI data]Number of patients coded as having Medicaid as payer source if they had any Medicaid as traditional fee-for-service or HMO (health maintenance organization) or managed care as current payment sources for home care at start of care or resumption of care | --- | --- | --- | Derived from: [CNSUS_MDCD_CNT / TOTRES]Number of residents whose primary payer source is Medicaid

--- Data not available.

NOTES: For survey data (ADSC and RCC), question wording refers to the National Study of Long-Term Care Providers (NSLTCP) services user questionnaires. Questionnaires and detailed documentation on survey variables are available from: https://www.cdc.gov/nchs/npals/questionnaires.htm. For administrative data (HHA, HOS, NH, IRF, and LTCH), when the data source is not specified, the source is Centers for Medicare and Medicaid Services Certification and Survey Provider Enhanced Reports (CASPER) data.

SOURCES: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018, and Centers for Medicare and Medicaid Services, 2017 and 2018.

Table VII

Health and functional characteristics of post-acute and long-term care services users, by sector

Characteristic | Definition | Survey data | | Administrative data
Characteristic | Definition | Adult day services center (ADSC) | Residential care community (RCC) | Home health agency (HHA) | Hospice (HOS) | Inpatient rehabilitation facility (IRF) | Long-term care hospital (LTCH) | Nursing home (NH)
Diagnosed with Alzheimer disease or dementia | Number of services users diagnosed with Alzheimer disease or dementia | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions? 2. Alzheimer’s disease or other dementia | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?2. Alzheimer’s disease or other dementia | Derived from: [ALZRDSD_BENE_CNT / BENE_CNT from Institutional Provider and Beneficiary Summary (IPBS) data]Number of beneficiaries meeting the chronic condition algorithm for Alzheimer’s broad classification, including dementia and utilizing the provider (Alzheimer’s disease and related disorders or senile dementia) | Derived from: [ALZRDSD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for Alzheimer’s broad classification, including dementia and utilizing the provider (Alzheimer’s disease and related disorders or senile dementia) | Derived from: [ALZRDSD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for Alzheimer’s broad classification, including dementia and utilizing the provider (Alzheimer’s disease and related disorders or senile dementia) | Derived from: [ALZRDSD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for Alzheimer’s broad classification, including dementia and utilizing the provider (Alzheimer’s disease and related disorders or senile dementia) | Derived from: [I4200_ALZHMR_CD, I4800_DMNT_CD from Minimum Data Set Active Resident Episode Table (MARET) data]Indicates whether the resident had an active diagnosis of Alzheimer’s disease in the last 7 days or indicates whether the resident had an active diagnosis of non-Alzheimer’s dementia, such as vascular or multi-infarct dementia; mixed dementia; or frontotemporal dementia, such as Pick’s disease and dementia related to stroke, Parkinson’s disease, or Creutzfeldt-Jakob disease in the last 7 days
Diagnosed with depression | Number of services users diagnosed with depression | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?11. Depression | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?11. Depression | Derived from: [DEPR_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for depression utilizing the provider | Derived from: [DEPR_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for depression utilizing the provider | Derived from: [DEPR_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for depression utilizing the provider | Derived from: [DEPR_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for depression utilizing the provider | Derived from: [I5800_DPRSN_CD from MARET data]Indicates if the resident had an active diagnosis of depression (other than bipolar) in the last 7 days
Diagnosed with diabetes | Number of services users diagnosed with diabetes | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?12. Diabetes | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?12. Diabetes | Derived from: [DIAB_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for diabetes utilizing the provider | Derived from: [DIAB_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for diabetes utilizing the provider | Derived from: [DIAB_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for diabetes utilizing the provider | Derived from: [DIAB_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for diabetes utilizing the provider | Derived from: [I2900_DM_CD from MARET data]Indicates whether the resident had an active diagnosis of diabetes mellitus (diabetic retinopathy or neuropathy) in the last 7 days
Diagnosed with arthritis | Number of services users diagnosed with arthritis | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?5. Arthritis or rheumatoid arthritis | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?5. Arthritis or rheumatoid arthritis | Derived from: [RAOA_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for rheumatoid or osteoarthritis and utilizing the provider | Derived from: [RAOA_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for rheumatoid or osteoarthritis and utilizing the provider | Derived from: [RAOA_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for rheumatoid or osteoarthritis and utilizing the provider | Derived from: [RAOA_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for rheumatoid or osteoarthritis and utilizing the provider | Derived from: [I3700_ARTHTS_CD from MARET data]Indicates whether the resident had an active diagnosis of arthritis in the last 7 days
Diagnosed with asthma | Number of services users diagnosed with asthma | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?6. Asthma | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?6. Asthma | Derived from: [ASTHMA_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for asthma and utilizing the provider | Derived from: [ASTHMA_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for asthma and utilizing the provider | Derived from: [ASTHMA_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for asthma and utilizing the provider | Derived from: [ASTHMA_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for asthma and utilizing the provider | ---
Diagnosed with chronic kidney disease | Number of services users diagnosed with kidney disease or chronic kidney disease | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?22. Kidney disease | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions? 22. Kidney disease | Derived from: [CKD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for chronic kidney disease and utilizing the provider | Derived from: [CKD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for chronic kidney disease and utilizing the provider | Derived from: [CKD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for chronic kidney disease and utilizing the provider | Derived from: [CKD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for chronic kidney disease and utilizing the provider | ---
Diagnosed with chronic obstructive pulmonary disease (COPD) | Number of services users diagnosed with COPD | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?10. COPD (chronic bronchitis or emphysema) | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?10. COPD (chronic bronchitis or emphysema) | Derived from: [COPD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for COPD and utilizing the provider | Derived from: [COPD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for COPD and utilizing the provider | Derived from: [COPD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for COPD and utilizing the provider | Derived from: [COPD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for COPD and utilizing the provider | ---
Diagnosed with heart disease | Number of services users diagnosed with heart disease | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?17. Heart disease (coronary or ischemic) | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions? 17. Heart disease (coronary or ischemic) | Derived from: [IHD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for ischemic heart disease and utilizing the provider | Derived from: [IHD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for ischemic heart disease and utilizing the provider | Derived from: [IHD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for ischemic heart disease and utilizing the provider | Derived from: [IHD_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for ischemic heart disease and utilizing the provider | Derived from: [I0400_CAD_CD, I0600_HRT_FAILR_CD, I4500_STRK_CD from MARET data]Indicates whether the resident had an active diagnosis of coronary artery disease, congestive heart failure, or stroke (CVA or TIA or Stroke) in the last 7 days
Diagnosed with high blood pressure or hypertension | Number of services users diagnosed with high blood pressure or hypertension | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?18. High blood pressure or hypertension | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?18. High blood pressure or hypertension | Derived from: [HYPERT_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for hypertension and utilizing the provider | Derived from: [HYPERT_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for hypertension and utilizing the provider | Derived from: [HYPERT_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for hypertension and utilizing the provider | Derived from: [HYPERT_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for hypertension and utilizing the provider | Derived from: [I0700_HYPRTNSN_CD from MARET data]Indicates whether the resident had an active diagnosis of hypertension in the last 7 days
Diagnosed with osteoporosis | Number of services users diagnosed with osteoporosis | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?27. Osteoporosis | As far as you know, has a doctor or other health professional ever diagnosed [sampled person’s initials] with any of the following conditions?27. Osteoporosis | Derived from: [OST_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for osteoporosis and utilizing the provider | Derived from: [OST_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for osteoporosis and utilizing the provider | Derived from: [OST_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for osteoporosis and utilizing the provider | Derived from: [OST_BENE_CNT / BENE_CNT from IPBS data]Number of beneficiaries meeting the chronic condition algorithm for osteoporosis and utilizing the provider | Derived from: [I3800_OSTPRS_CD from MARET data]Indicates whether the resident had an active diagnosis of osteoporosis in the last 7 days
Assistance with eating | Number of services users needing any assistance with eating.Assistance refers to needing any help or supervision from another person or use of assistive devices. | Needs assistance = 1 No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need to eat, like cutting up food? 1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Needs assistance = 1No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need to eat, like cutting up food?1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Derived from: [MSR_342_VAL from Outcome-Based Quality Improvement (OBQI)]Number of patients coded as needing any assistance with eating if they: are able to feed self independently but require meal setup or intermittent assistance or supervision from another person; require a liquid, pureed, or ground meat diet; are unable to feed self and must be assisted or supervised throughout the meal or snack; are able to take in nutrients orally and receive supplemental nutrients through a nasogastric tube or gastrostomy; are unable to take in nutrients orally and are fed nutrients through a nasogastric tube or gastrostomy; or are unable to take in nutrients orally or by tube feeding | --- | Derived from: [EAT_ADMSN_CD from IRF-PAI] Number of patients needing assistance with eating including: 1) Helper—complete dependence or total assistance; 2) Helper—complete dependence or maximal assistance; 3) Helper—modified dependence or moderate assistance; 4) Helper—modified dependence or minimal assistance; 5) Helper—modified dependence or supervision | --- | Derived from: [CNSUS_EATG_ASTD_CNT, CNSUS_EATG_DPNDNT_CNT / CNSUS_RSDNT_CNT]Number of residents coded as needing any assistance with eating if they require supervision, limited or extensive assistance from staff, or full staff performance every time during entire 7-day period. If the facility routinely provides “setup” activities (e.g., opening containers, buttering bread, and organizing the tray) and if this is the extent of assistance provided for the resident, the resident was coded as not needing any assistance with eating
Assistance with dressing | Number of services users needing any assistance with dressing. Assistance refers to needing any help or supervision from another person or use of assistive devices. | Needs assistance = 1No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need to dress?1. Need help or supervision2. Use of an assistance device 3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Needs assistance = 1 No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need to dress?1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Derived from: [MSR_335_VAL and MSR_336_VAL from OBQI]Number of patients coded as needing any assistance with dressing if: they are able to dress upper and lower body without assistance, if clothing and shoes are laid out or handed to the patient; someone must help the patient put on upper body clothing or undergarments, slacks, socks or nylons, and shoes; or patient depends entirely upon another person to dress the upper and lower body | --- | Derived from: [DRSG_UPR_ADMSN_CD, DRSG_LWR_ADMSN_CD from IRF-PAI] Number of patients needing assistance with dressing including: 1) Helper—complete dependence or total assistance;2) Helper—complete dependence or maximal assistance;3) Helper—modified dependence or moderate assistance; 4) Helper—modified dependence or minimal assistance;5) Helper—modified dependence or supervision | --- | Derived from: [CNSUS_DRS_ASTD_CNT; CNSUS_DRS_DPNDNT_CNT / CNSUS_RSDNT_CNT]Number of residents coded as needing any assistance with dressing if they require supervision, limited or extensive assistance from staff, or full staff performance every time during entire 7-day period. If the facility routinely set out clothes for all residents, and this is the only assistance the resident receives, the resident was coded as not needing any assistance with dressing
Assistance with toileting | Number of services users needing any assistance with using bathroom. Assistance refers to needing any help or supervision from another person or use of assistive devices. | Needs assistance = 1No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need to use the bathroom or toileting?1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Needs assistance = 1No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need to use the bathroom or toileting?1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Derived from: [MSR_339_VA from OBQI]Number of patients coded as needing any assistance with toileting if: the patient is able to manage toileting hygiene and clothing management without assistance if supplies or implements are laid out for the patient; someone must help the patient to maintain toileting hygiene or adjust clothing; or the patient depends entirely upon another person to maintain toileting hygiene. Toileting hygiene refers to the patient’s current ability to maintain perineal hygiene safely, or adjust clothes or incontinence pads before and after using toilet, commode, bedpan, and urinal. If managing ostomy, it includes cleaning area around stoma, but not managing equipment | --- | Derived from: [TOILTG_ADMSN_CD from IRF-PAI] Number of patients needing assistance with toileting including:1) Helper—complete dependence or total assistance;2) Helper—complete dependence or maximal assistance;3) Helper—modified dependence or moderate assistance;4) Helper—modified dependence or minimal assistance;5) Helper—modified dependence or supervision | --- | Derived from: [CNSUS_TOILT_ASTD_CNT, CNSUS_TOILT_DPNDNT_CNT / CNSUS_RSDNT_CNT]Number of residents coded as needing any assistance with toileting if they require supervision, limited or extensive assistance from staff, or full staff performance every time during entire 7-day periodIf all that is done for the resident is to open a package (e.g., a clean sanitary pad), the resident was coded as not needing any assistance with toileting.
Assistance with bathing | Number of services users needing any assistance with bathing or showering. Assistance refers to needing any help or supervision from another person or use of assistive devices. | Needs assistance = 1No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need to bathe or shower?1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Needs assistance = 1 No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need to bathe or shower?1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Derived from: [MSR_337_VAL from OBQI]Number of patients coded as needing any assistance with bathing if the patient is: with the use of devices, able to bathe self in shower or tub independently, including getting in and out of the tub or shower; able to bathe in shower or tub with the intermittent assistance of another person; able to participate in bathing self in shower or tub, but requires presence of another person throughout the bath for assistance or supervision; unable to use the shower or tub, but able to bathe self independently with or without the use of devices at the sink, in chair, or on commode; unable to use the shower or tub, but able to participate in bathing self in bed, at the sink, in bedside chair, or on commode, with the assistance or supervision of another person throughout the bath; or unable to participate effectively in bathing and is bathed totally by another person | --- | Derived from: [BATHG_ADMSN_CD from IRF-PAI] Number of patients needing assistance with bathing including: 1) Helper—complete dependence or total assistance;2) Helper—complete dependence or maximal assistance;3) Helper—modified dependence or moderate assistance;4) Helper—modified dependence or minimal assistance;5) Helper—modified dependence or supervision | --- | Derived from: [CNSUS_BATHG_ASTD_CNT, CNSUS_BATHG_DPNDNT_CNT / CNSUS_RSDNT_CNT]Number of residents coded as needing any assistance with bathing if they require supervision, physical help limited to transfer only or in part of bathing activity, or full staff performance every time during entire 7-day periodIf the facility provides setup assistance to all residents, such as drawing water for a tub bath or laying out bathing materials, and the resident requires no other assistance, the resident was coded as not needing any assistance with bathing.
Assistance with walking or locomotion | Number of services users needing any assistance with walking or locomotion. Assistance refers to needing any help or supervision from another person or use of assistive devices. | Needs assistance = 1No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need for locomotion or to walk?1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Needs assistance = 1No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need for locomotion or to walk?1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Derived from: [MSR_341_VAL from OBQI]Number of patients coded as needing any assistance with ambulation or locomotion if they are: able to independently walk on even and uneven surfaces and negotiate stairs with or without railings without use of an assistive device, with the use of a one-handed assistive device, or with the use of a two-handed device; able to walk only with the assistance of another person at all times; chairfast, unable to ambulate but are able to wheel self independently; chairfast, unable to ambulate and unable to wheel self; or bedfast, unable to ambulate or be up in a chair | --- | Derived from: [WLK_ADMSN_CD from IRF-PAI]Number of patients needing assistance with walking or locomotion including:1) Helper—complete dependence or total assistance;2) Helper—complete dependence or maximal assistance;3) Helper—modified dependence or moderate assistance;4) Helper—modified dependence or minimal assistance;5) Helper—modified dependence or supervision | --- | Derived from: [CNSUS_INDPNDNT_MBLTY_CNT / CNSUS_RSDNT_CNT]Number of residents who require no help or oversight; or help or oversight was provided only one or two times during the past 7 days. Do not include residents who use a cane, walker, or crutchSubtracted from CNSUS_RSDNT_CNT
Assistance with transferring | Number of services users needing any assistance with transferring. Assistance refers to needing any help or supervision from another person or use of assistive devices. | Needs assistance = 1No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need to transfer in and out of a chair?1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Needs assistance = 1No assistance = 2Derived from: Which types of assistance, if any, does [sampled person’s initials] currently need to transfer in and out of a bed or chair? 1. Need help or supervision2. Use of an assistance device3. Both4. Need no assistanceIf 1, 2, or 3, then = 1; if 4, then = 2. | Derived from: [MSR_340_VAL from OBQI]Number of patients coded as needing any assistance with transferring if they are: able to transfer with minimal human assistance or with use of an assistive device; able to bear weight and pivot during the transfer process but unable to transfer self; unable to transfer self and are unable to bear weight or pivot when transferred by another person; bedfast, unable to transfer but are able to turn and position self in bed; bedfast, unable to transfer and are unable to turn and position self | --- | Derived from: [BED_CHR_WC_ADMSN_CD from IRF-PAI]Number of patients needing assistance with transferring from bed, chair, or wheelchair including:1) Helper—complete dependence or total assistance; 2) Helper—complete dependence or maximal assistance;3) Helper—modified dependence or moderate assistance; 4) Helper—modified dependence or minimal assistance; 5) Helper—modified dependence or supervision | --- | Derived from: [CNSUS_TRNSFR_ASTD_CNT, CNSUS_TRNSFR_DPNDNT_CNT / CNSUS_RSDNT_CNT]Number of residents who require help moving between surfaces, including, to or from bed, chair, wheelchair, or standing positionsExcludes transfers to or from the bath or toilet. If the facility routinely provides “setup” assistance to all residents, such as handing the equipment (e.g., sliding board) to the resident, and this is the only assistance required, the resident was coded as not needing assistance with transferring.

--- Data not available.

NOTES: For survey data (ADSC and RCC), question numbers refer to the order in National Study of Long-Term Care Providers (NSLTCP) services user questionnaires. Questionnaires and detailed documentation on survey variables are available from: https://www.cdc.gov/nchs/nsltcp/nsltcp_questionnaires.htm. For administrative data (HHA, HOS, and NH), when the data source is not specified, the source is Centers for Medicare and Medicaid Services Certification and Survey Provider Enhanced Reports (CASPER).

SOURCES: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018, and Centers for Medicare and Medicaid Services, 2017 and 2018.

Table VIII

Adverse events among post-acute and long-term care services users, by sector

Characteristic | Definition | Survey data | | Administrative data
Characteristic | Definition | Adult day services center (ADSC) | Residential care community (RCC) | Home health agency (HHA) | Hospice (HOS) | Inpatient rehabilitation facility (IRF) | Long-term care hospital (LTCH) | Nursing home (NH)
Overnight hospital stay | Number of services users who were discharged from an overnight hospital stay | Was [sampled person’s initials] discharged from an overnight hospital stay in the past 90 days? Exclude trips to the hospital emergency department that did not result in an overnight hospital stay.1 = Yes2 = No3 = Don’t knowDon’t know was coded as missing data. | Was [sampled person’s initials] discharged from an overnight hospital stay in the past 90 days? Exclude trips to the hospital emergency department that did not result in an overnight hospital stay. 1 = Yes2 = No3 = Don’t knowDon’t know was coded as missing data. | Derived from: [MSR_447_VAL from Outcome-Based Quality Improvement (OBQI)]To which inpatient facility has the patient been admitted?1 = Hospital | --- | --- | --- | Number of residents in 2018 Minimum Data Set Active Resident Episode Table (MARET) data file, with an overnight hospital stay, defined as MARET residents with at least one inpatient hospitalization claim in the 2018 Medicare Provider Analysis and Review, where the inpatient hospitalization discharge occurred after the nursing home admission date and during the 2018 calendar year
Emergency department visits | Number of services users who had emergency department visits | During the past 90 days, was [sampled person’s initials] treated in a hospital emergency department? 1 = Yes2 = No3 = Don’t knowDon’t know was coded as missing data. | During the past 90 days, was [sampled person’s initials] treated in a hospital emergency department? 1 = Yes2 = No3 = Don’t knowDon’t know was coded as missing data. | Derived from: [MSR_426_VAL from OBQI Case Mix Roll-up data]Since the last time Outcome and Assessment Information Set data were collected, has the patient utilized a hospital emergency department (includes holding or observation)? | --- | --- | --- | ---
Falls | Number of services users who had falls | Derived from: By falls we mean any fall, slip, or trip in which [sampled person’s initials] lost balance and landed on the floor or ground or at a lower level. Please include falls that occurred at your adult day services center or off-site, whether or not [sampled person’s initials] was injured, and whether or not anyone saw [sampled person’s initials] fall or caught them. As best you know, during the past 90 days, how many falls has [sampled person’s initials] had? | Derived from: By falls we mean any fall, slip, or trip in which [sampled person’s initials] lost balance and landed on the floor or ground or at a lower level. Please include falls that occurred at your residential care community or off-site, whether or not [sampled person’s initials] was injured, and whether or not anyone saw [sampled person’s initials] fall or caught them. As best you know, during the past 90 days, how many falls has [sampled person’s initials] had? | --- | --- | --- | --- | Derived from: [J1800_FALL_LAST_ASMT_CD from MARET data]Has the resident had any falls since admission or the prior assessment, whichever is more recent?
Length of stay | Nursing home residents categorized by short-stay (residents had been admitted less than 100 days from assessment date) and long-stay (admitted for 100 days or more) | --- | --- | --- | --- | --- | --- | Derived from: [LAST_TRGT_DT and A1600_ENTRY_DT from MARET data]If LOS <= 100, then SHORTSTAY_100 = 1; if LOS > 100, then SHORTSTAY_100 = 0.

--- Data not available.

NOTES: For survey data (ADSC and RCC), question wording refers to the National Study of Long-Term Care Providers services user questionnaires. Questionnaires and detailed documentation on survey variables are available from: https://www.cdc.gov/nchs/npals/questionnaires.htm. For administrative data (HHA, HOS, NH, IRF, and LTCH), when the data source is not specified, the source is Centers for Medicare and Medicaid Services Certification and Survey Provider Enhanced Reports data.

SOURCES: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018, and Centers for Medicare and Medicaid Services, 2017 and 2018.