# Appendix I. Technical Notes

## Data Sources

This report uses data from multiple sources, including two main sources: 1) administrative data, including certification, assessment, and claims from the Centers for Medicare & Medicaid Services (CMS) on home health agencies, hospices, nursing homes, inpatient rehabilitation facilities (IRFs), and long-term care hospitals (LTCHs); and 2) establishment-based survey data from the National Center for Health Statistics (NCHS) for residential care communities (RCCs) and adult day services centers (ADSCs). Data for all seven sectors were obtained for comparable time periods, where feasible.

### Study Redesign

In 2018, the two survey sectors (ADSC and RCC) of the National Study of Long-Term Care Providers (NSLTCP) were redesigned to provide only national estimates, and a separate module was added that was designed to randomly sample two services users from eligible and participating providers. This redesign also changed the way estimates from CMS administrative person-level data sources were managed and how the estimates were derived compared with 2012, 2014, and 2016. These methodological changes may affect comparisons with estimates from earlier versions of this report. The methodological changes and their implications are addressed in this appendix.

### Administrative Data: Home Health Agencies, Hospices, Nursing Homes, IRFs, and LTCHs

#### Provider-level data

Provider-level data files were from the Certification and Survey Provider Enhanced Reports (CASPER) system. CASPER data are collected to support the survey and certification regulatory functions of CMS, and every home health agency, hospice, nursing home, IRF, and LTCH in the United States that is certified to provide services under Medicare, Medicaid, or both is included. The CASPER data used in this report includes active providers up to the third quarter of 2018. Providers are located in the United States and District of Columbia; this report excludes American Samoa, Guam, Puerto Rico, and the U.S. Virgin Islands. The availability of variables in each file and frequency of data collection varies by sector because of different reporting requirements and time intervals for certification for each of the providers. For most sectors, CASPER files provided data on the number of providers, U.S. census regions, metropolitan statistical area derived from zip codes, ownership type, certification status, chain status, staffing levels, and services provision. Like previous versions of this report, except for nursing homes, all CASPER data files were merged with aggregated user-level data files to calculate the average number of people served annually and the categories of the number of people served (size), and to replace outliers in staffing levels using size-specific means. For these variables, missing data is minimal for providers that were not represented in the respective user-level file. The nursing home CASPER data file was not merged with user data files because it included the number of residents (census) that could be used to calculate the above-mentioned estimates.

Home health agency file—Included 11,499 home health agencies; about 77.5% were Medicare- and Medicaid-certified, 21.4% were Medicare-certified only, and 1.4% were Medicaid-certified only. About 82.5% of these home health agencies completed a certification survey during the last 3 years (including 55.6% during the last 2 years).

Hospice file—Included 4,693 hospices; information on the type of certification (Medicare-only, Medicaid-only, or both) was not available. CMS requires certification surveys of Medicare hospices every 6–8 years, on average (44). However, most Medicare hospices (83.1%) completed a certification survey during the last 3 years (including 57.2% during the last 2 years).

Nursing home file—Included 15,595 nursing homes; about 93.0% were Medicare- and Medicaid-certified, 4.6% were Medicare-certified only, and 2.3% were Medicaid-certified only. Nearly all of these nursing homes (98.9 %) completed a certification survey during the last 18 months (including 83.0% during the last 12 months).

IRF file—Included 1,157 facilities; about 96.0% were Medicare- and Medicaid-certified, 4.2% were Medicare-certified only, and no facilities were Medicaid-certified only. About 35% completed a certification survey during the last 3 years.

LTCH file—Included 390 hospitals; almost 77.0% were Medicare- and Medicaid-certified, 23.1% were Medicare-certified only, and no hospitals were Medicaid-certified only. About 46.4% completed certification surveys during the last 3 years.

#### User-level data

User-level data were obtained from different sector-specific CMS assessment and claims data sources. In this report, the user-level data for home health (from Outcome-Based Quality Improvement [OBQI]), nursing homes (from Minimum Data Set Active Resident Episode Table [MARET]), and IRF (from Inpatient Rehabilitation Facility-Patient Assessment Instrument [IRF-PAI]) were analyzed at the person level and not merged to CASPER. The Institutional Provider and Beneficiary Summary (IPBS) claims data files (for home health agencies, hospice, IRF, and LTCH), which are provided to NCHS as aggregated data, were also analyzed separately and not merged to CASPER. Therefore, no user data are missing.

#### Home health patients

OBQI Agency Patient-Related Characteristics Report data (formerly known as Case Mix Roll-up data) are aggregated episode-level data from the Outcome and Assessment Information Set (OASIS). OBQI data were used as the primary source of information on home health patients whose episode of care ended at any time in calendar year 2017 (discharges), regardless of payment source. These data included home health patients who received services from Medicare- and Medicaid-certified home health providers in states where those agencies were required to meet the Medicare Conditions of Participation.

A total of 4,940,270 patients from 11,180 agencies were included. The file was used to estimate the number of annual home health patients, agency size, use rates, and the percentages of home health patients by age, sex, Medicaid assistance recipient status, needing any assistance with activities of daily living (ADLs), having any hospitalizations, and having any emergency department visits.

IPBS home health data were also used because OBQI data did not use racial and ethnic categories and information on patients’ diagnoses that were comparable to those available in data sources for other sectors in this report. The IPBS data file contained information on home health patients for whom Medicare-certified home health agencies submitted a Medicare claim at any time in calendar year 2017. The data file includes 4,082,193 patients from 10,857 agencies. This file was used to estimate percentages of home health patients by race and ethnicity and selected diagnosed conditions.

#### Hospice patients

The IPBS hospice data file contained information on hospice patients for whom Medicare-certified hospice agencies submitted a Medicare claim at any time in calendar year 2017. Given that 93.0% of hospice agencies were Medicare certified in 2007 (based on findings from the 2007 National Home and Hospice Care Survey) and that no other data source was available on hospice patients, IPBS hospice data were assumed to provide current coverage and information on most hospice patients. The total number of hospice patients was 1,562,524 from 4,517 hospices. These data were used to estimate the number of annual hospice patients, hospice size, use rates, and the percentages of hospice patients by age, sex, race and ethnicity, and selected diagnosed conditions.

#### Nursing home residents

The CASPER nursing home file for the third quarter of 2018 included census information on selected measures for 1,321,184 current residents of 15,595 nursing homes. This information was collected using Form CMS-672 (Resident Census and Conditions of Residents) and represents the facility at the time of the certification survey. Resident census data were used for the number of current residents, nursing home size, use rates, and the percentages of residents with ADL limitations.

MARET data contained assessment information on all active residents who were residing in a Medicare- or Medicaid-certified nursing home on the last day of the third quarter of 2018, regardless of payment source. CMS defines an active resident as “a resident whose most recent assessment transaction is not a discharge and whose most recent transaction has a target date (assessment reference date for an assessment record or entry date for an entry record) less than 150 days old. If a resident has not had a transaction for 150 days, then that resident is assumed to have been discharged.” The number obtained from MARET was 1,372,477 nursing home residents from 15,525 nursing homes. These data were used to estimate the percentages of residents by age, sex, race and ethnicity, and selected diagnosed conditions. The measurement of short-stay (43.6% of residents admitted for fewer than 100 days) and long-stay (56.4% of residents admitted for 100 days or more) nursing home residents was derived from the nursing home admission and assessment dates in MARET.

Medicare Provider Analysis and Review (MedPAR) inpatient claims data from calendar year 2018 were merged with 2018 MARET data using a unique beneficiary ID number to measure overnight hospitalizations among current nursing home residents who were also Medicare beneficiaries. This method was used because the MARET data exclude residents whose last assessment was a discharge, which would include discharges to a hospital. After merging MedPAR and MARET, a total of 591,905 Medicare beneficiaries were in both the MARET and MedPAR files. Qualifying hospitalizations were measured by having any hospital discharge that occurred after the nursing home admission date.

#### Inpatient rehabilitation facility patients

The IPBS IRF data file contained information on IRF patients for whom Medicare-certified IRFs submitted a Medicare claim at any time in calendar year 2017. The total number of IRF patients was 380,430 from 1,124 facilities. These data were used to estimate the annual number of IRF patients, facility size, use rates, and the percentages of patients by age, sex, race and ethnicity, and selected diagnosed conditions.

IRF-PAI contains data at admission and upon discharge for all Medicare Part A fee-for-service patients who received services under Part A from an IRF. Patient assessments are required for facilities classified for payment under Medicare’s IRF prospective payment system, and at least 60% of the total inpatient population must require IRF treatment for 1 or more of 13 conditions (26). The number of IRF patients was 416,416 from 1,126 facilities. This data set was used to estimate percentages of patients needing assistance with ADLs.

#### Long-term care hospital patients

The IPBS LTCH data file contained information on patients for whom Medicare-certified LTCHs submitted a Medicare claim at any time in calendar year 2017. IPBS LTCH data were assumed to provide current coverage and information on most patients. The total number of LTCH patients was 115,882 from 416 hospitals. These data were used to estimate the annual number of patients, hospital size, use rates, and the percentages of patients by age, sex, race and ethnicity, and selected diagnosed conditions.

### Survey Data: ADSCs and RCCs

NCHS designed and conducted surveys for the ADSC and RCC components of the fourth wave of NSLTCP in 2018. The 2018 NSLTCP surveys of ADSCs and RCCs were conducted from July 2018 to February 2019. Documentation for the 2018 RCC and ADSC NSLTCP surveys, which includes a survey methodology report, survey-specific readme documents, and downloadable examples of the provider and services user survey questionnaires, is available from: https://www.cdc.gov/nchs/npals/questionnaires.htm#tabs-1-2. The NSLTCP questionnaires consist of topics common or comparable across all seven sectors (core topics) and topics that are specific to a particular sector (sector-specific topics). To make comparisons across sectors easier, the core topics for the primary data collection for ADSCs and RCCs were designed to be as similar as possible to the core topics and wording available through the CMS administrative data.

The 2018 RCC and ADSC surveys differed from previous waves in that they comprised three survey components for each sector:

1. Eligibility screener—Administered to sampled ADSCs and RCCs via computer-assisted telephone interview (CATI) to determine eligibility before mailing the Provider Module questionnaire.
2. Provider module—Questionnaire was sent to eligible respondents via mail, or respondents were asked to complete the survey online.
3. Services user module—Questionnaire was administered via CATI. Telephone interviewers instructed respondents to randomly sample two of all currently enrolled participants or current residents. Respondents then answered interview questions about each of the two randomly sampled users.

#### Eligibility screener

Unlike previous waves, the 2018 NSLTCP used a separate screener questionnaire, which was administered by CATI. The instrument was designed to assess whether ADSCs and RCCs met the study definition and were eligible to participate. The ADSC screener included questions about licensure, average daily attendance, and enrollment. The RCC screener included seven questions about licensure, number of beds and residents, provision of 24-hour supervision, number of meals, assistance with activities of daily living, and whether they exclusively serve people with intellectual disabilities or severe mental illnesses.

#### Provider and services user questionnaires

The ADSC and RCC provider questionnaires were administered by mail and Internet, with nonresponse follow-up by telephone. They collected information about the operations, practices, user demographics, services offered, and staffing profile of sampled ADSCs and RCCs. The services user questionnaire was administered by telephone using CATI. The respondents were instructed on the methodology for randomly selecting two services users. The services user questionnaire included questions about demographics, length of stay, charges and payment sources, health and functional status, health care use, and service use. Most of the questions were the same for ADSCs and RCCs; however, a few sector-specific questions were included as well.

#### ASDCs

The sampling frame obtained from the National Adult Day Services Association (NADSA) contained ADSCs that self-identified as adult day care, adult day services, or adult day health services centers that were in operation as of November 2017. After removing duplicates, the final frame consisted of 5,478 ADSCs that were included in data collection efforts. The set of eligibility criteria for study participation was determined by self-report in the screener section of the questionnaire. To be eligible, ADSCs had to:

- Be licensed or certified by the state specifically to provide adult day services or accredited by the Commission on Accreditation of Rehabilitation Facilities, or authorized or otherwise set up to participate in Medicaid (Medicaid state plan, Medicaid waiver, or Medicaid managed care), or as part of a Program of All-Inclusive Center for the Elderly.
- Have an average daily attendance of at least one participant based on a typical week.
- Have at least one participant enrolled at the designated center at the time of the survey.

As a result of using these eligibility criteria, all responding eligible centers participated in Medicaid or were in some way regulated by the state. From a frame of 6,361 ADSCs, 1,650 were randomly selected for the survey. Of the 1,650 sampled ADSCs, eligibility could not be determined for 543. Among those cases where eligibility could be determined (1,107), 917 (83%) were eligible and 190 (17%) were ineligible because they did not meet the survey criteria or were out of business. However, 543 ADSCs (33%) could not be contacted, so the final eligibility status of these centers was unknown. Eligibility rate was calculated by the number of known eligible ADSCs divided by the total number of ADSCs with known eligibility status. ADSCs that were invalid or out of business and those that screened out as ineligible were classified as “known ineligibles.” Using the eligibility rate of 83%, a proportion of these ASDCs of unknown eligibility was estimated to be eligible; therefore, 450 ADSCs of unknown eligibility were assumed as eligible. The total number of eligible ADSCs was estimated as 1,367 (917 plus 450). Of the 1,367 in-scope and presumed in-scope ADSCs, 672 of them completed the provider questionnaire, for a weighted response rate (for differential probabilities of selection) of 50%. To account for ADSCs of unknown eligibility, the weights of the ADSCs with known eligibility were adjusted upward based on the proportion of ADSCs that were actually known to be eligible. Adjustments were also made to account for nonresponse. Response rates are calculated using standards set by American Association of Public Opinion Research (AAPOR). AAPOR Response Rate #4 calculations include assumptions of eligibility among potential respondents that are not interviewed. AAPOR Response Rate #4 formula was used to calculate response rates for ADSCs (completed questionnaires divided by [completed eligible questionnaires] plus [eligibility rate multiplied by cases of unknown eligibility]).

Two participants were randomly selected from eligible ADSCs that agreed to participate in the study. A questionnaire was completed for a total of 1,255 participants from 630 ADSCs, resulting in a participant response rate of 46%. About 66% of ADSCs completed both provider and at least one participant module, and the rest of the ADSCs completed either the provider or the participant module.

#### RCCs

The sampling frame was constructed from lists of licensed RCCs obtained from the state licensing agencies in each of the 50 states and the District of Columbia. The 2018 NSLTCP used the same definition of RCC and the same approach to create the sampling frame (45) that was used for the 2010 National Survey of Residential Care Facilities (NSRCF) (46). To be eligible for the study, an RCC must be licensed, registered, listed, certified, or otherwise regulated by the state to:

- Provide room and board with at least two meals a day and around-the-clock, onsite supervision.
- Help with personal care, such as bathing and dressing or health-related services, such as medication management.
- Have four or more licensed, certified, or registered beds.
- Have at least one resident currently living in the RCC.
- Serve a predominantly adult population.

RCCs licensed to exclusively serve people with severe mental illnesses, intellectual disability, or developmental disability, as well as nursing homes, were excluded.

From a frame of 43,770 RCCs, 2,090 were randomly selected for the survey. Of the 2,090 sampled RCCs, eligibility could not be determined for 977. Among those for which eligibility could be determined (1,113), 857 (77%) were eligible and 256 (23%) were ineligible because they did not meet the survey criteria or were out of business. However, 977 RCCs (33%) could not be contacted; therefore, the final eligibility status of these RCCs was unknown. The eligibility rate is calculated by the number of known eligible RCCs divided by the total number of RCCs with known eligibility status. RCCs that were invalid or out of business and RCCs that screened out as ineligible were classified as known ineligibles. Using the eligibility rate of 77%, a proportion of these RCCs of unknown eligibility was estimated to be eligible; 752 RCCs of unknown eligibility were assumed to be eligible. The total number of eligible RCCs was estimated as 1,609 (857 plus 752). Of the 1,609 in-scope and presumed in-scope RCCs, 503 completed the provider questionnaire, for a weighted response rate (for differential probabilities of selection) of 30%. Response rates are calculated using standards set by AAPOR, specifically AAPOR’s Response Rate #4. AAPOR Response Rate #4 calculations include assumptions of eligibility among potential respondents that are not interviewed. AAPOR Response Rate #4 formula was used to calculate response rates for RCCs (completed questionnaires divided by [completed eligible questionnaires] plus [eligibility rate multiplied by cases of unknown eligibility]). To account for the RCCs of unknown eligibility, the weights of the RCCs with known eligibility were adjusted upward based on the proportion of communities that were actually known to be eligible. Adjustments were also made to account for nonresponse.

Two residents were randomly selected from eligible RCCs that agreed to participate. A questionnaire was completed for a total of 904 residents from 452 RCCs, resulting in a response rate of 28%. About 48.9% of RCCs completed both the provider and at least one resident module, and the remaining RCCs either completed the provider module or the resident module.

#### Differences in number of RCCs estimated in 2010, 2012, 2014, 2016, and 2018

Estimates of the number of RCC providers varied between the 2010 NSRCF and the 2012 NSLTCP. NCHS assessed these differences and concluded that they were largely related to the eligibility differences between the 2010 NSRCF and the 2012 NSLTCP. While both surveys used the same eligibility criteria, overall screener-based eligibility dropped from 81.0% in the 2010 NSRCF to 67.1% in the 2012 NSLTCP (Table I). The screener-based eligibility rate was computed based on RCCs that completed the screening questions (completed eligible divided by [completed eligible plus completed ineligible]).

Table I

Eligibility rate among residential care communities, by bed size and survey year

Eligible community | National Study of Long-Term Care Providers | | | | 2010 National Survey of Residential Care Facilities
Eligible community | 2018 | 2016 | 2014 | 2012 | 2010 National Survey of Residential Care Facilities
| Percent
Overall | 77.0 | 73.8 | 80.7 | 67.1 | 81.0
Bed size | Rate
Small (4–10 beds) | 61.3 | 55.5 | 65.3 | 45.8 | 63.6
Medium (11–25 beds) | 75.0 | 74.5 | 81.0 | 68.5 | 82.8
Large (26–100 beds) | 85.1 | 86.9 | 91.7 | 82.4 | 94.5
Extra large (more than 100 beds) | 92.1 | 91.2 | 93.8 | 85.5 | 95.9

SOURCES: National Center for Health Statistics, National Study of Long-Term Care Providers, 2012, 2014, 2016, and 2018, and National Survey of Residential Care Facilities, 2010.

This decrease in the screener-based eligibility rate was most pronounced for providers with small bed sizes (4–10 beds): a decrease from 63.6% in 2010 to an estimated 45.8% in 2012. Given that the 2012 NSLTCP (n = 11,690) had a much larger sample than NSRCF (n = 3,605), and that small bed size providers make up the largest proportion of all RCCs, the lower eligibility rate in 2012 compared with 2010 among small-sized RCCs had a large effect on the differences in the eligibility rate for the two surveys.

The discrepancy in eligibility between the 2010 NSRCF and the 2012 NSLTCP was likely due to differences in data collection modes used in 2010 (interviewer-administered CATI screener followed by an in-person interview for eligible communities) and 2012 (primarily respondent self-administered screener and questionnaire completed by mail or Internet), and the resulting differences in how the respondents who self-administered the questionnaire interpreted the eligibility questions. In the 2012 NSLTCP, the most common eligibility criterion that providers, particularly small bed size RCCs, did not meet was provision of onsite, 24-hour supervision. Some respondents using the self-administered modes (hard-copy questionnaire or Internet questionnaire) likely did not fully understand this question and may have screened themselves out of the study erroneously. For more information, see “Long-Term Care Services in the United States: 2013 Overview” (available from: https://www.cdc.gov/nchs/data/series/sr_03/sr03_037.pdf) and the 2012 RCC data file (available from: https://www.cdc.gov/nchs/data/nsltcp/NSLTCP_RCC_Readme_RDC_Release.pdf). Cognitive testing was conducted to assess these eligibility questions, and preliminary findings supported this hypothesis. To address these differences, NCHS revised the NSLTCP eligibility question on whether the RCC provided 24-hour supervision. The eligibility question asking whether the RCC provided 24-hour supervision is Question 4 on the 2012 questionnaire (https://www.cdc.gov/nchs/data/nsltcp/2012_NSLTCP_Residential_Care_Communities_Questionnaire.pdf) and Question 6 on the 2014 questionnaire (https://www.cdc.gov/nchs/data/nsltcp/2014_NSLTCP_Residential_Care_Communities_Questionnaire.pdf).

Results from the 2014 wave indicated that the overall eligibility rate increased to 80.7%, similar to the 2010 NSRCF rate. However, the 2014 eligibility rates for all bed size categories except small providers (4–10 beds) were slightly lower compared with the 2010 NSRCF (Table I) which may be attributed to mode differences between 2010 and 2014. In 2016, the overall eligibility rate decreased to 73.8%. Decline in eligibility was observed in all bed size categories, but mostly among the small and medium categories. In 2018, the overall eligibility rate increased to 77%, and the eligibility rate for small RCCs was similar to the 2010 eligibility rate. The estimated national number of RCCs ranged from 31,100 in 2010; 22,200 in 2012; 30,200 in 2014; and 28,900 in 2016 to 31,400 in 2018. The number of beds were estimated at 971,900 in 2010; 851,400 in 2012; 1,006,300 in 2014; 996,100 in 2016; and 1,183,600 in 2018 (Table II). For more information about differences in eligibility rates over survey years, see “Eligibility Rate Differences Among Residential Care Communities: 2010 National Survey of Residential Care Facilities and 2012–2018 National Study of Long-Term Care Providers” (available from: https://dx.doi.org/10.15620/cdc:115807).

Table II

Weighted number and percent distribution of residential care communities, by bed size and survey year

Characteristic | National Study of Long-Term Care Providers | | | | | | | | 2010 National Survey of Residential Care Facilities
Characteristic | 2018 | | 2016 | | 2014 | | 2012 | | 2010 National Survey of Residential Care Facilities
Characteristic | Number | Percent | Number | Percent | Number | Percent | Number | Percent | Number | Percent
Number of residential care communities | 31,400 | 100.0 | 28,900 | 100.0 | 30,200 | 100.0 | 22,200 | 100.0 | 31,100 | 100.0
Small (4–10 beds) | 14,700 | 46.7 | 13,200 | 45.6 | 14,500 | 47.9 | 9,300 | 41.7 | 15,400 | 50.0
Medium (11–25 beds) | 4,000 | 12.8 | 4,400 | 15.3 | 4,500 | 14.9 | 3,700 | 16.8 | 4,900 | 16.0
Large (26–100 beds) | 9,800 | 31.1 | 9,100 | 31.5 | 9,100 | 30.1 | 7,300 | 32.7 | 8,700 | 28.0
Extra large (more than 100 beds) | 2,900 | 9.3 | 2,200 | 7.7 | 2,100 | 7.0 | 1,900 | 8.7 | 2,100 | 7.0
Number of beds | 1,183,600 | 100.0 | 996,100 | 100.0 | 1,006,300 | 100.0 | 851,400 | 100.0 | 971,900 | 100.0
Small (4–10 beds) | 90,400 | 7.6 | 81,800 | 8.2 | 89,600 | 8.9 | 64,700 | 7.6 | 96,700 | 9.9
Medium (11–25 beds) | 71,900 | 6.1 | 76,500 | 7.7 | 76,900 | 7.6 | 86,900 | 10.2 | 86,800 | 8.9
Large (26–100 beds) | 565,300 | 47.8 | 518,300 | 52.0 | 522,600 | 51.9 | 434,800 | 51.1 | 493,800 | 50.8
Extra large (more than 100 beds) | 456,000 | 38.5 | 319,500 | 32.1 | 317,200 | 31.5 | 265,000 | 31.1 | 294,600 | 30.3

SOURCES: National Center for Health Statistics, National Study of Long-Term Care Providers, 2012, 2014, 2016, and 2018, and National Survey of Residential Care Facilities, 2010.

### Population Bases for Computing Rates

Populations used for computing rates of national supply by region (Figure 3) and use of services by people aged 65 and over per 1,000 people aged 65 and over were obtained from the U.S. Census Bureau’s Population Estimates Program. The program produces estimates of the population for the United States, its states, counties, cities, and towns, and for the Commonwealth of Puerto Rico and its municipalities. Demographic components of population change (births, deaths, and migration) were produced at the national, state, and county levels of geography. Additionally, housing unit estimates were produced for the country, states, and counties. Population estimates for each state and territory were not subject to sampling variation because the sources used in the demographic analysis were complete counts. For a more detailed description of the methodology, see: https://www.census.gov/programs-surveys/popest.html.

### Comparing NSLTCP Estimates With Estimates From Other Data Sources

#### Administrative data

Home health agencies—Available estimates from the 2017–2018 data files were compared with estimates from 2015–2016 CASPER and OBQI home health data in NSLTCP (5), the 2020 and 2019 Medicare Payment Advisory Commission (MedPAC) Medicare Payment Policy report to Congress using 2018 and 2017 data, respectively (2,47), and CMS Home Health Compare data in 2018 (48). The 2018 CASPER included 700 fewer agencies compared with 2016 CASPER data, but the number of agencies in MedPAC and Home Health Compare were similar. In 2018 CASPER, 82% of agencies were for profit compared with 81% in 2016 CASPER, 88% in 2018 MedPAC (2), and 81.7% in 2018 Home Health Compare. The percentages of agencies with social work, therapeutic, and skilled nursing services were similar in the 2018 and 2016 NSLTCP and Home Health Compare. More than 4.9 million patients were included in the 2017 OBQI compared with 4.5 million in the 2015 OBQI and 3.4 million Medicare beneficiaries using home health care in MedPAC in 2017 (47).

Hospices—Selected estimates from the 2017–2018 hospice data files were compared with 2016 CASPER and 2015 IPBS hospice data (5), 2017 and 2018 MedPAC data (2,47), and CMS Hospice Compare in 2018 (49). About 350 more agencies were included in 2018 CASPER compared with 2016 CASPER (4,350 agencies), but a similar number of home health agencies in MedPAC (2) and Hospice Compare in 2018. Similar percentages of for-profit agencies were seen across all sources. About 1.6 million patients were included in the 2017 IPBS compared with 1.5 million patients in the 2017 MedPAC (47) and 1.4 million in the 2015 IPBS.

Nursing homes—Available estimates from the 2018 nursing home files were compared with 2016 NSLTCP data (5), 2018 data in MedPAC (2), and 2018 CMS Nursing Home Compare (50). The number of nursing homes in 2018 CASPER, 2016 CASPER, and 2018 Nursing Home Compare data were similar; however, the number of nursing homes was about 600 fewer as reported in MedPAC, which is limited to Medicare-certified nursing homes. The percentage of for-profit, metropolitan, and Medicare- and Medicaid-certified nursing homes were similar across all data sources. More than 1.3 million residents were reported on a given day in 2018 CASPER and 2018 Nursing Home Compare compared with 1.4 million in 2016 CASPER and 1.5 million Medicare beneficiaries in MedPAC in 2018.

Staffing information obtained from 2018 CASPER is statistically significantly lower compared with 2016 CASPER because, beginning in 2018, CMS required nursing homes to upload payroll information to the Payroll Based Journal (PBJ) system (51). According to requirements of the Affordable Care Act (Section 6106), this new method of reporting requires facilities to submit agency and contract care staffing data based on payroll rather than self-reported information. Comparisons show that previous reports of CASPER staffing levels were statistically significantly higher than PBJ staffing information (52), which is consistent with comparisons between 2018 data in this report (Appendix III, Table X) and the previous report (4).

IRF—Selected estimates from the 2017–2018 IRF files were compared with estimates in MedPAC (2,47) and 2018 IRF CMS Compare data (53). The number of IRFs and percentage of for-profit IRFs were similar across all three data sources. A total of 375,100 patients were reported in 2017 IPBS data and 355,000 patients were reported in 2017 MedPAC (47).

LTCH—Selected estimates from the 2017–2018 LTCH files were compared with MedPAC (2,47) and 2018 LTCH CMS Compare data (54). The number of LTCHs was lower in MedPAC in 2018 (374) than in CASPER (390) and LTCH Compare (401), with a similar average capacity in CASPER and LTCH Compare. The percentage of for-profit hospitals was similar in CASPER (67.2%) and LTCH Compare (65.8%), compared with 78.0% in MedPAC in 2018 (2). About 116,000 LTCH patients were in 2017 IPBS data compared with about 103,000 patients in MedPAC 2017 data (47).

#### Survey data

Estimates from the 2018 ADSC and RCC components of NSLTCP were compared with estimates from the earlier waves of NSLTCP. Differences between the 2010 NSRCF and the 2012, 2014, 2016, and 2018 NSLTCP RCC survey estimates for the number of RCCs, beds, and residents are discussed earlier in this appendix. The 2018 estimates for selected provider and user characteristics for both ADSCs and RCCs were found to be comparable with earlier waves of the study, with a few exceptions.

### Differences Between Survey Waves

The ADSC and RCC components of NSLTCP have evolved over the four waves of the study in terms of new questions, changes in question wording and response categories, as well as data editing. A comparison of the questions used in the four waves lists all of the new items added to NSLTCP (https://www.cdc.gov/nchs/data/npals/2012-2018-Survey-Content-Crosswalk-508.pdf). In addition to new questions, the question wording and response categories for several questions were revised in the 2018 wave, as listed here. Some of these differences may have led to differences in data editing methods, as well as differences in estimates between the waves.

- Response categories for the revenue source question in the ADSC questionnaires (Questions 11 in 2012, 9 in 2014, and 10 in 2016 and 2018) were revised after each wave. The 2012 and 2014 questions included six response categories: Medicaid, Medicare, other government, out-of-pocket payment by the participant family, private insurance, and other. In 2014, a brief definition was added to the Medicaid response category to specify that this category include Medicaid managed care programs. In 2016, the number of response categories increased to eight, with the “other government” category broken into three separate categories: Older Americans Act, Veterans Administration, and other federal, state, or local government. The Medicaid category definition was also revised to include revenue from a Medicaid state plan, Medicaid waiver, Medicaid managed care, or California regional center. In 2018, another response category was added, “Program of All-Inclusive Care for the Elderly (PACE).”
- Response categories for questions on services provided in the ADSC questionnaires (Questions 19 in 2012, 12 in 2014, 30 in version A and 27 in version B in 2016, and 23 in 2018) and the RCC questionnaires (Questions 16 in 2012, 15 in 2014, 28 in version A and 29 in version B in 2016, and 26 in 2018) were revised after each wave. In 2012, each service item had four response categories indicating that the service was “not provided,” “provided only by residential care community/adult day services center employees,” “provided only by others through arrangement,” or “provided by both residential care community/adult day services center employees and others through arrangement.” In 2014, respondents were asked to mark one or more of five categories indicating that the service was provided by “paid residential care community/adult day services center employees,” “arranging for and paying outside vendors,” “arranging for outside vendors paid by others,” “referral,” or “none of these apply/not provided.” In 2016, the response options were revised to four categories indicating that an RCC or ADSC “provides the service by paid residential care community/adult day services center employees,” “arranges for the service to be provided by outside services,” “refers residents/participants or family to outside service providers,” or “does not provide, arrange, or refer for this service.” These response options stayed the same in the 2018 questionnaire.
- Formatting and wording for staffing questions in the ADSC (Questions 23 in 2012, 14 in 2014, 31–33 in version A and 28–30 in version B in 2016, and 28 and 37 in 2018) and RCC (Questions 26 in 2012, 17 in 2014, 29–31 in version A and 30–32 in version B in 2016, and 31 and 41 in 2018) questionnaires changed between the four waves. In 2012, respondents had the option of providing either the separate numbers of full-time and part-time staff or the number of full-time equivalent (FTE) staff. In 2014, the response categories included only the number of full-time staff and the number of part-time staff (not FTEs). In both 2012 and 2014, the staffing questions were formatted as a block to include both employees and contract staff. In 2016, respondents continued to provide the number of full-time and part-time staff (not FTEs), but the questions were formatted in two separate blocks for employees and contract staff. Also in 2016, respondents could skip the contract staff block if they answered “no” to a stem question about having any contract or agency staff. The 2018 questions repeated the 2016 version but included an additional set of questions about turnover.

The differences in formatting in 2016 led to some methodological changes to the staffing data edits in 2016 compared with previous waves. Details about differences in how the staffing data were edited in 2014 and 2016 are provided in the “Data Description and Usage (Readme)” documents for the ADSC survey (https://www.cdc.gov/nchs/data/nsltcp/NSLTCP_2016_ADSC_Readme_RDC.pdf) and the RCC survey (https://www.cdc.gov/nchs/data/nsltcp/NSLTCP_2016_RCC_Readme_RDC.pdf).

- For the first three waves of NSLTCP, the services user questions were aggregated at the provider level, and variation occurred in how the aggregate questions were asked. The ADL question about walking or locomotion in the ADSC (Questions 32g in 2012, 19f in 2014, and 16f in 2016) and RCC (Questions 34g in 2012, 22f in 2014, and 17f in 2016) questionnaires changed. The 2012 and 2016 waves included a brief description stating that assistance with locomotion or walking included using a cane, walker, wheelchair, or help from another person; this description was not included in the 2014 wave.
- The question on falls in the ADSC (Questions 22 in 2014 and 25 in version A in 2016) and RCC (Questions 25 in 2014 and 23 in version A in 2016) questionnaires changed. The 2014 wave asked about the number of falls (any) in the last 90 days and directed respondents to include onsite and offsite falls. The 2016 wave added instructions for respondents to include falls that occurred in the RCC or ADSC or offsite, whether the resident or participant was injured, and whether anyone saw the resident or participant fall or caught them. Respondents were also asked to count only one fall per resident or participant who fell, even if the resident or participant fell more than once, and to include a resident or participant who had a fall in the last 90 days even if they were currently in a hospital or rehabilitation facility.
- In 2018, a separate services user module was used to ask questions about two randomly selected services users in each eligible and participating ADSC and RCC. Using a separate services user module may have resulted in differences in services user estimates between 2018 and earlier years of the study. To assess if estimates of services user characteristics varied by source of services user data (aggregated services user questions or a separate services user module), a small set of questions about services users was included in the provider module (as in previous years) and the services user module. These included questions about the age and sex of services users and whether they needed assistance with bathing and eating. Differences in estimates of age and sex did not vary significantly by source of services user data (provider module or services user module). However, estimates of need for assistance with bathing varied significantly for both sectors, and estimates of need for assistance with eating varied significantly for ADSCs by source of data (provider module or services user module). The ADSC provider module estimated 27.4% and 35.0% of participants needing assistance with eating and bathing, respectively; 41.4% and 74.8% of participants in the services user module were reported to need assistance with eating and bathing, respectively. For RCCs, 64.6% and 77.3% of residents were reported as needing assistance with bathing in the provider or services user module, respectively. These differences indicate an underestimation of need for assistance for the selected ADLs in the provider module. Similar underestimation of other services user characteristics may exist but was difficult to assess in the absence of comparable variables in the provider and services user modules.

## Data Analysis

Results describing providers were analyzed at the agency or facility level, and most user-level data were analyzed at the individual level, except for some aggregated user-level data files in the administrative data sectors as described previously. Findings from administrative data were treated as sample based, and population standard errors were calculated to account for some random variability associated with the data.

For the survey data, point estimates and standard errors were calculated using appropriate design and weight variables to account for complex sampling, when applicable. Statistical analysis weights were computed as the product of two components: the sampling weight and adjustment for unknown eligibility due to nonresponse. To adjust the ADSC and RCC weights for unknown eligibility, the SUDAAN procedure WTADJUST (47) was used; the procedure uses a constrained logistic model to predict known eligibility and to compute the unknown eligibility adjustment factors for the weights. Standard errors for survey data were computed using Taylor series linearization. All estimates meet NCHS guidelines for reliability or proportions (55).

### Variance Estimates

#### Administrative data

The home health, hospice, nursing home, IRF, and LTCH data files were created using CMS administrative data. The files represented 100% of the CMS regulated providers and users or beneficiaries of those providers at the specific time that the data set was constructed, and they were not subject to sampling variability. Therefore, the standard errors could be seen as being zero. However, there might be some random variability associated with the numbers. For example, if the administrative data were drawn at a different time, the estimates might be different. The data also are subject to potential data entry and other reporting errors. To account for these types of variability, the administrative data estimates were treated as a simple random sample, providing conservative standard errors for the random variation that might be associated with the data.

#### Survey data: ADSCs and RCCs

Data for ADSCs and RCCs were collected using nationally representative samples. Consequently, the RCC and ADSC estimates were subject to sampling variability and nonresponse variability. The variability for the ADSC and RCC estimates was treated as if they were from stratified samples without replacement. The initial estimation strata for ADSCs are defined by region and metropolitan statistical area (MSA), and for RCCs the initial estimation strata were defined by region, size, and MSA.

### Statistical Significance Tests

All statements in this report describing differences in estimates indicate that statistical testing was performed, and the differences between two-point estimates were determined to be statistically significant at the 0.05 level. Differences among sectors were evaluated using t tests. All statistical significance tests were two sided using p < 0.05 as the significance level. Lack of comment regarding the difference between any two statistics does not necessarily mean that the difference was tested and found not to be statistically significant. Data analyses were performed using SAS version 9.3, the SAS-callable SUDAAN version statistical package (56), and Stata/SE 14.0 (57). Individual estimates may not sum to totals because estimates were rounded.

### Data Editing

Data files were examined for missing values and inconsistencies. To minimize cases with missing values and inconsistencies, RCC and ADSC survey instruments were programmed to show critical items with missing values in the CATI and Internet applications, to inform respondents that an answer was required, and to include data validations such as asking respondents to check an answer if it was not the expected number. For instance, if responses to items that needed to total the number of RCC residents or ADSC participants did not match the total, respondents were reminded to check their responses.

For the ADSC and RCC survey data, selected resident- or participant-level variables were imputed (such as age, race, and sex). Although administrative data were also reviewed for missing values and inconsistencies, the files did not go through the same data cleaning and editing as the survey data.

For both survey and administrative data, staffing information was edited in the same manner. Outliers were defined as values two standard deviations above or below the size-specific mean for a given staff type, where size was defined as number of people served. When calculating the size-specific mean for a given staff type, cases were coded as missing if the number of FTE registered nurse, FTE licensed practical or vocational nurse, or FTE personal care aide employees was greater than 999, or if the number of FTE social work employees or FTE activities director or staff employees was greater than 99. Additional edits were made to the staffing variables, some of which differed from earlier waves of NSLTCP. For the definitions and categories of number of people served for each sector, see Appendix II.

#### Missing data

Cases with missing data were excluded from analyses on a variable-by-variable basis. Variables used in this report had 10% or fewer cases with missing data.

## Limitations

### Differences in Question Wording Among Data Sources

While every effort was made to match question wording in the NSLTCP surveys to the administrative data available through CMS, some differences remain and may affect comparisons between these two data sources (for example, capacity and reference periods used for adverse events). When available and appropriate, findings were presented on a given topic for all sectors. However, due to two types of data-related differences, for some topics in the report, information was provided for some but not all seven sectors.

The first type of data-related difference was due to the settings served by the seven sectors. For example, home health agencies were not residential and, consequently, it was not relevant to discuss the number of beds in this sector, while it was relevant to present this data for nursing homes, RCCs, IRFs, and LTCHs.

The second difference was attributable to differences among the administrative data sources used for nursing homes, home health agencies, hospices, IRFs, and LTCHs. For example, the CASPER data did not include information on whether home health agencies offered mental health or counseling services, but they did include this information for nursing homes and hospices. The NSLTCP RCC and ADSC surveys included additional content that was not presented in this report because no comparable data existed in the CMS administrative data (such as electronic health records and health information exchange). NCHS produced Data Briefs and weighted estimates tables that presented additional results on ADSCs and RCCs, using survey data not included in this overview report. These latest reports are available from: https://www.cdc.gov/nchs/npals/studyresults.htm.

### Differences in Time Frames Among Data Sources

Different data sources had different time frames or reference periods. For instance, user-level data used for home health agencies (OBQI and IPBS home health data) were from patients who received services at any time in calendar year 2017. In contrast, survey data on RCC residents and ADSC participants and CMS data on nursing home residents were from current services users in 2018. In this report, “current” participants or residents in 2018 refers to those participants enrolled in the ADSC, or residents living in the nursing home or RCC, on the day of data collection in 2018, rather than the total number of participants ever enrolled in the center or residents ever living in the nursing home or RCC at any time throughout the 2018 calendar year. As such, the estimated number of ADSC participants represents current participants in 2018. The estimated number of home health patients represents patients who ended care in 2017 (discharges). The estimated number of hospice, IRF, and LTCH patients represents patients who received care at any time in 2017. The estimated number of nursing home residents represents current residents in 2018. The estimated number of RCC residents represents current residents in 2018. Given these differences in denominator, comparisons across all seven sectors were not feasible for some variables.