# Key Findings

In 2018, about 69,000 paid, regulated post-acute and long-term care services providers in seven major sectors served more than 9.5 million people in the United States.

- Post-acute and long-term care services were provided by 4,200 adult day services centers, 11,500 home health agencies, 4,700 hospices, 15,600 nursing homes, 31,400 assisted living and similar residential care communities, 1,200 inpatient rehabilitation facilities, and 400 long-term care hospitals (Appendix III, Table IX).
- In 2018, an estimated 251,100 current participants were enrolled in adult day services centers; 1,321,200 people were current residents in nursing homes; and 918,700 current residents were living in residential care communities. In 2017, about 4,940,300 patients were discharged from home health agencies; 1,562,500 patients received services from hospices; 380,400 patients received services from inpatient rehabilitation facilities; and 115,800 patients received services from long-term care hospitals (Appendix III, Table XII).

Supply varied by region and sectors differed by ownership and chain status.

- The supply of residential care beds per 1,000 people aged 65 and over was higher than the supply of nursing home beds in the West, while nursing home beds outnumbered residential care community beds in all other regions. The capacity of adult day services centers was lowest in the Midwest. Moreover, the capacity of inpatient rehabilitation facilities and long-term care hospitals was lowest in the West compared with their capacity among other regions (Figure 3).
- Most home health agencies, hospices, nursing homes, residential care communities, and long-term care hospitals were for profit, while a minority of adult day services centers and inpatient rehabilitation facilities were for profit (Figure 4). Most nursing homes and residential care communities were chain-affiliated, in contrast to adult day services centers, the minority of which were chain-affiliated (Figure 5).

Figure 3 Post-acute and long-term care services provider capacity per 1,000 people aged 65 and over, by sector and region: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 3 is a bar chart showing provider capacity of post-acute and long-term care services per 1,000 people aged 65 years and over by sector and region in the United States in 2018.

Figure 4 Percent distribution of post-acute and long-term care services providers, by sector and ownership: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 4 is a stacked bar chart showing percent distribution of post-acute and long-term care services providers by sector and ownership in the United States in 2018.

Figure 5 Percentage of post-acute and long-term care services providers that are chain-affiliated, by sector: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 5 is a bar chart showing percentage of post-acute and long-term care services providers that are chain-affiliated by sector in the United States in 2018.

Nearly 1.6 million nursing employee full-time equivalents (FTEs)—including registered nurses (RNs), licensed practical or vocational nurses (LPNs or LVNs), and aides—and about 35,000 social work employee FTEs worked in the seven sectors.

- The relative distribution of nursing and social work employee FTEs varied across sectors; the most common employee FTEs were aides in adult day services centers, nursing homes, and residential care communities, while RNs were the most common employee FTEs in home health agencies, hospices, and inpatient rehabilitation facilities. LPNs or LVNs were the most common employee FTEs in long-term care hospitals (Figure 9).

Figure 9 Total number and percent distribution of nursing and social work full-time equivalent employees, by sector and staff type: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 9 is a stacked bar chart showing total number and percent distribution of nursing and social work full-time equivalent employees by sector and staff type in the United States in 2018.

Sectors differed in their average staffing levels for nursing, social work, and activities employees.

- Among the three sectors where nursing staff levels (RNs, LPNs or LVNs, and aides) could be examined, the average total nursing staff hours per resident or participant day was higher in residential care communities than in nursing homes and adult day services centers (Figure 11).
- The average social work staffing level was higher in residential care communities than in adult day services centers and nursing homes, and the average activities staffing level in adult day services centers was more than in nursing homes and residential care communities.

Figure 11 Average staff hours per resident or participant per day, by sector and staff type: United States, 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 11 is a stacked bar chart showing average staff hours per resident or participant per day by sector and staff type in the United States in 2018.

Daily-use rates among people aged 65 and over per 1,000 people aged 65 and over varied by sector.

- The daily-use rate was higher for nursing homes than for residential care communities and adult day services centers (data not shown).

Post-acute and long-term care services users varied by sector in their demographic and health characteristics and functional status.

- Adult day services center participants tended to be younger than services users in other sectors (Figure 20).
- Adult day services center participants were the most racially and ethnically diverse among the seven sectors (Figure 22).
- More than one-quarter of services users in each of the seven sectors had a diagnosis of Alzheimer disease or other dementias, and more than one-half of services users in each sector had a diagnosis of hypertension (Figure 24). However, the prevalence of these and eight other reported diagnosed chronic conditions varied widely between sectors.
- Fewer residential care community residents needed assistance with four of six activities of daily living (ADLs; dressing, toileting, transferring, and eating) than services users in other sectors (Figure 25).

Figure 20 Percent distribution of post-acute and long-term care services users, by sector and age group: United States, 2017 and 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 20 is a stacked bar chart showing percent distribution of post-acute and long-term care services users by sector and age group in the United States in 2017 and 2018.

Figure 22 Percent distribution of post-acute and long-term care services users, by sector and race and Hispanic origin: United States, 2017 and 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 22 is a stacked bar chart showing percent distribution of post-acute and long-term care services users by sector and race and Hispanic origin in the United States in 2017 and 2018.

Figure 24 Percentage of post-acute and long-term care services users with selected diagnoses, by sector: United States, 2017 and 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 24 is a bar chart showing percentage of post-acute and long-term care services users with selected diagnoses by sector in the United States in 2017 and 2018.

Figure 25 Percentage of post-acute and long-term care services users needing any assistance with activities of daily living, by sector and activity: United States, 2017 and 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 25 is a bar chart showing percentage of post-acute and long-term care services users needing any assistance with activities of daily living by sector and activity in the United States in 2017 and 2018.

Adverse events among post-acute and long-term care services users varied by sector.

- Compared with adult day participants and residential care residents, more home health patients had overnight hospital stays and emergency department visits (Figure 26).
- More residential care residents had falls compared with adult day participants and nursing home residents.

Figure 26 Percentage of post-acute and long-term care services users with overnight hospital stays, emergency department visits, and falls, by sector: United States, 2017 and 2018

NOTES: Estimates are based on data from the 2018 National Study of Long-Term Care Providers (NSLTCP). See Technical Notes for details on data sources and estimation.

SOURCE: National Center for Health Statistics, National Study of Long-Term Care Providers, 2017–2018.

Figure 26 is a bar chart showing percentage of post-acute and long-term care services users with overnight hospital stays, emergency department visits, and falls by sector in the United States in 2017 and 2018.

Nursing home resident characteristics varied by length of stay.

- Short-stay (fewer than 100 days) residents differed from long-stay (100 days or more) residents by age and sex, and in the prevalence of numerous diagnosed conditions, overnight hospital stays, and falls (Appendix III, Table XIII).

## Acknowledgments

The authors are grateful to the many people who provided technical expertise and assistance in implementing the 2018 National Study of Long-Term Care Providers (NSLTCP) and in developing this report.

This report was edited and produced by the National Center for Health Statistics (NCHS) Office of Information Services, Information Design and Publishing Staff: editor Laura Drescher, typesetter Kyung Park, and graphic designer Simon McCann.

The authors are indebted to the directors and administrators of the assisted living and similar residential care communities and adult day services centers, and their designated staff, who took time to complete the questionnaires. This report would lack information on these sectors without their participation.

The authors recognize the following organizations for their vital contributions in successfully completing the 2018 NSLTCP adult day services center and residential care community surveys: ADvancing States, American Seniors Housing Association (ASHA), Argentum, Center for Excellence in Assisted Living (CEAL), LeadingAge, National Adult Day Services Association (NADSA), and National Center for Assisted Living (NCAL). For promoting participation in the 2018 surveys, the authors thank Maribeth Bersani (Argentum), Jeanne McGlynn Delgado (ASHA), Brendan Flinn (LeadingAge), Donna Hale (NADSA), Ruth Katz (LeadingAge), Stephen Maag (LeadingAge), Lisa Peters-Beumer (NADSA), Lance Roberts (NADSA), Martha Roherty (ADvancing States), Lindsay Schwartz (NCAL and CEAL), and Claire Shanley (CEAL).

The authors thank the members of the 2011 NSLTCP Work Group, whose expertise helped guide the NSLTCP survey content. Members, with affiliations at the time of the 2011 meeting, include: Jean Accius, AARP; Gretchen Alkema, The SCAN Foundation; Nicholas Castle, University of Pittsburgh; Thomas Clark, American Society of Consultant Pharmacists; Joel Cohen, Agency for Healthcare Research and Quality; Rosaly Correa-de-Araujo, U.S. Department of Health and Human Services; Holly Dabelko-Schoeny, The Ohio State University; Frederic Decker, Health Resources and Services Administration; Elena Fazio, Administration for Community Living; Michael Furukawa, Office of the National Coordinator for Health Information Technology; Mary George, Centers for Disease Control and Prevention (CDC); Stacie Greby, CDC; Stuart Hagen, Congressional Budget Office; Christa Hojlo, Department of Veterans Affairs (VA); Teresa Johnson, NADSA; Judith Kasper, Johns Hopkins University; Enid Kassner, AARP; Ruth Katz, Office of the Assistant Secretary for Planning and Evaluation (ASPE); Gavin Kennedy, ASPE; Mary Jane Koren, The Commonwealth Fund; Dave Kyllo, NCAL; Sheila Lambowitz, Centers for Medicare & Medicaid Services (CMS); Karen Love, CEAL; William Marton, ASPE; Lisa Matthews-Martin, American Health Care Association; Anne Montgomery, U.S. Senate Special Committee on Aging; Vincent Mor, Brown University; Richard Nahin, CDC; Carol O’Shaughnessy, National Health Policy Forum; Doug Pace, Long-Term Quality Alliance; Georgeanne Patmios, National Institute on Aging; Carol Regan, Paraprofessional Healthcare Institute; Robin Remsburg, University of North Carolina at Greensboro; Robert Rosati, Visiting Nurse Service of New York; Emily Rosenoff, ASPE; James Scanlon, ASPE; Daniel Schoeps, VA; Margo Schwab, Office of Management and Budget; Carol Spence, National Hospice and Palliative Care Organization; Nimalie Stone, CDC; Robyn Stone, LeadingAge; Mary St. Pierre, National Association for Home Care & Hospice; Nicola Thompson, CDC; Daniel Timmel, CMS; Julie Weeks, NCHS; Janet Wells, National Consumer Voice for Quality Long-Term Care; and Cheryl Wiseman, CMS.

Under a contract with NCHS, RTI International implemented the 2018 NSLTCP surveys. The authors gratefully acknowledge the talented and dedicated staff at RTI International for their contributions to the design and successful implementation of the 2018 NSLTCP surveys, especially Angela Greene, Melissa Hobbs, Katherine Mason, Katelan McDaniel, Mai Nguyen, Linda Lux, Kristie Porter, Rebecca Powell, and Celia Eicheldinger.

The authors are grateful for the technical support and assistance from staff at CMS and the Research Data Assistance Center who helped identify and obtain needed administrative data sources throughout this project, specifically Stephanie Bartee, Dovid Chaifetz, Wesley Choi, Angela Jannotta, Matt McFalls, Jennifer Reese, Cheryl Sample, Samantha Saykao, and Elizabeth Thompson. Special thanks to Anne Valentino and Tanya Boyd in NCHS’ Division of Health Care Statistics for helping with the purchase of administrative data files from CMS.

We specially acknowledge the contributions made by Vincent Rome during data collection, data file development, and in preparation of the report.