# Application of the JATS for Reuse Accessibility Recommendations

This paper explores the JATS4R recommendations for tagging Journal Article Tag Suite (JATS) XML articles with a focus on advancing accessibility in scholarly publishing. While the JATS Standard provides a flexible XML framework, the JATS4R Recommendations offer best practices for using JATS to promote consistent and accessible content. Divergences between the JATS Standard and JATS4R are expected, as JATS4R is more prescriptive to meet user accessibility needs across various platforms.

We emphasize the importance of prioritizing accessibility throughout the publication workflow, highlighting the Accessibility Recommendation's goal of enabling accessible presentations of JATS XML articles. Addressing potential challenges, such as alt-text creation and table heading requirements, we propose solutions that balance practical constraints with the imperative to meet global accessibility standards (e.g., WCAG, Section 508, EU Accessibility Act). These recommendations are not mandatory but serve as pathways to compliance with legal and ethical accessibility requirements.

The paper also introduces tools for verifying accessibility in structured content, from pre-JATS XML stages through publication, including checklists for authors, editors, and publishers, and guidance on exporting accessibility metadata. The JATS4R Validator and Schematron rules are also presented.

Finally, we discuss the importance of integrating accessibility checks throughout the document lifecycle. By embedding these practices early in the workflow, organizations can achieve more accessible, compliant, and reusable content with greater efficiency and reduced cost.

## Introduction

The Journal Article Tag Suite (NISO Z39.96-2024; JATS) is an XML standard widely adopted in the publishing industry for encoding and exchanging scholarly content [1][2]. As a flexible and comprehensive standard, JATS accommodates the diverse requirements of publishers, enabling them to represent article metadata and content effectively. However, this flexibility can lead to variations in its implementation, which poses challenges for consistency and interoperability.

To address this, the JATS for Reuse (JATS4R)[3] initiative was established to create a set of community-driven recommendations aimed at regularizing the use of JATS XML.[4] These recommendations provide a more prescriptive subset of JATS designed to promote uniformity to enable content sharing across publishers and platforms and reuse of the content in the future.

Differences exist between the JATS standard and JATS4R recommendations, which is not unexpected, given that JATS4R's primary goal is not to replace the standard but to provide practical guidance that aligns with common user needs: to define best tagging practices to make the content of the future set of JATS articles more useful (reuseable). The NISO JATS Standing Committee, who is responsible for the standard, defines the article structure and tries to make the models as useful and applicable as possible. Their goal is to make (and maintain) a useful standard.[5]

To oversimplify this, the NISO JATS Standing Committee is primarily concerned with how article structure is represented. JATS4R is primarily concerned with how article content is represented. Narrowing the scope to a subset of the broader XML model, JATS4R helps publishers coalesce around consistent practices, addressing real-world challenges without compromising the flexibility of the underlying standard.

An essential area of focus for both JATS and JATS4R is accessibility. By prioritizing accessibility upstream—at the stage of content creation and encoding—publishers can ensure that scholarly content is inclusive and usable by diverse audiences.

## The Accessibility Recommendation

### The goal

The primary goal of the JATS4R Accessibility Recommendation is to ensure that enough information is captured in the JATS XML to facilitate the creation of accessible presentations of an article. It is important to note that the aim is not to make the JATS XML itself accessible, but rather to use it as a tool to meet accessibility standards.

### Does it go "too far" or is it "too hard" to apply?

We don't think so. These recommendations are not mandatory requirements but are designed to help meet government accessibility policies where applicable. Examples of such policies include:

- Section 508 (US)[6]
- 2025 European (EU) Accessibility Act 2019/882[7]
- Canada's EN 301 549 Accessibility Requirements for ICT products and services[8]
- Japanese Industrial Standards (JIS) X8341-3[9]

To provide creators of JATS XML with the best chance of successful compliance with legal and ethical initiatives like those mentioned above, all of our recommendations are aligned with existing accessibility standards, such as the Web Content Accessibility Guidelines (WCAG).[10] And while we acknowledge that compliance with some of these items may present challenges, we also believe that many of these items, such as providing alt-text for every image, are fundamental to creating accessible content.

### The burdensome things and how to deal with them

#### Alt-text

One of the significant challenges in implementing the JATS4R Accessibility Recommendations is the creation of alternative text (<alt-text>) for all images. This task can be both costly and time-consuming, particularly when dealing with extensive backfiles, as the process of generating alt-text is not something that can be easily automated without intensive editorial input and oversight.

To address this issue for backfiles, one potential solution is to employ image recognition models and pre-trained or custom large language models (LLMs) to generate alt-text. However, it is still crucial to ensure that there is thorough editorial review to verify the accuracy of the descriptions. Alt-text generated by artificial intelligence (AI) can sometimes be inaccurate, and in contexts such as medical or technical fields, even minor inaccuracies can have serious repercussions. Editorial review helps mitigate the risk of liability that could arise from incorrect information being provided by AI.

For future content, we suggest moving the creation of alt-text to the initial stages of the content creation process. By integrating alt-text early on, it becomes a much more manageable task. To facilitate this, we recommend training authors, editors, and publishers on best practices for alt-text creation. Additionally, we have provided specific suggestions on how to manage this process effectively in the section titled Testing/Verifying your content Pre-JATS XML below.

#### Table headings (<th> tags)

Another area of concern is the use of table headings. Feedback we've received indicates that in some fields, it is common to use tables to present structured information without headings. However, this practice can pose accessibility challenges, because headings are essential for making tables comprehensible for users using screen readers.

To address this issue, it is important to consider whether the information presented in the table can be conveyed in a non-tabular format. If a non-tabular format is not feasible, consider adding headings to the table to enhance readability for all users. This approach ensures that the information is accessible and comprehensible to everyone.

Consider the following examples:

##### Table without headings

Table 1

Passive voice: | The essay was written by the student.
Active voice: | The student wrote the essay.

##### Rewritten as normal text

Passive voice: The essay was written by the student.

Active voice: The student wrote the essay.

##### Rewritten as a table with headings

Table 2

Voice | Example
Passive voice: | The essay was written by the student.
Active voice: | The student wrote the essay.

These are very simple examples, and there might be legitimate cases that are too difficult to represent in this way, but we feel strongly that an effort should be made to avoid tables without headings whenever possible.

## Testing/Verifying your Content Pre-JATS XML

While the JATS4R Schematron tests (discussed below) are great, it’s even better if you can address accessibility as early as possible in your workflow. Additionally, there are a handful of things the Schematron can’t check for you, so you’ll need to think about where in your workflow people can start thinking about accessibility. Ideally, anyone who interacts with the document at any point will be able to bring their own skills and perspectives to enhance the document’s accessibility and decrease the risk of expensive mitigation efforts later.

Some questions to consider in the pre-XML stage of your document’s lifecycle:

- Are you editing structured content? Is your view of the document navigable through the various heading levels? If you’re starting in Word, you can use the Navigation Pane or Outline view to review your overall document structure and check the nesting of your heading levels.
- Who is responsible for writing the alt-text for images? If you aren’t providing guidance to your authors about how to write good alt-text, are your editors expected to fill in this missing information for the author to review? If you’re waiting until your published document is up on a hosting platform and letting a vendor supply post-publication alt-text, how are you ensuring that the alt-text is both accurate and contextually relevant? Are there any implications for copyright, permissions, or licensing if your alt-text is AI-generated?
- Do you use any screening tools to check the quality and color contrast on your graphics? Are you still using red and green as contrasting colors? Those can be indistinguishable to color-blind readers. Is there sufficient contrast between colors in your graphics? Light text on a light background or dark text on a dark background isn’t particularly readable to anyone. If you have text inside the image, does it need to be there, or can it be moved to the caption? Try to keep text inside a figure as minimal as possible.
- Are you using high-resolution graphics? How do they scale at different sizes? Can a reader zoom in without losing image quality? Schematron is great but it can’t look at your graphics.
- Are the equations created in a way that can easily be converted to MathML, or are they simple graphics? If your workflow still publishes math as graphics, you need alt-text on those graphics, too.
- Are your tables images? They shouldn’t be. Tables need proper headers so the scope can be clearly communicated to everyone.
- Do you have a way to verify that special characters are actually the correct character entity or value, and not just something that looks similar? This is also not something Schematron can check for you.
- Do you have audio and video descriptions and captions?
- If you have interactive content or other multimedia, is there an accessible version?
- Do all your links have descriptive text about where they’re going? If all your links say “Click Here” then that can cause confusion for screen-readers, especially if the links are read out of context.
- How clickable are your citations? For readers with physical disabilities, it’s much easier to click “Figure 1” than to click just the number “1” or any other single character.

In an ideal world, your submissions system would be able to do at least some amount of accessibility checking for you, along with capturing important metadata. If your submissions platform isn’t helping you with this, maybe that’s something that could be improved in the coming years. Implementing accessibility checks from the ground up in this way could enable future systems to ingest and export accessibility metadata, which can then be communicated to other systems.

Creating born-accessible content might mean a significant change to your editorial workflow and author instructions, and it might not be something you can implement immediately, but you can still keep accessibility in mind throughout every stage of the document’s workflow. It’s easier and less costly to create accessible published documents if you can begin with a structured document that uses proper heading levels, has alt-text that can be edited and reviewed along with the graphics, and uses appropriate table headers.

## Testing your JATS XML with Schematron

The JATS4R Validator is a tool provided to assist publishers and content creators in evaluating their XML content against JATS4R recommendations. While it provides a structured method for identifying potential issues, it is important to understand its purpose, limitations, and the broader context of what "validity" entails in the context of tagging style checking.

### Understanding "Validity" in Tagging Style Checking

Strictly speaking, "validity" in XML validation is adherence to the structural and syntactic rules defined by a schema [Document Type Definition (DTD) W3C Schema (XSD), or RELAX NG RNG/RNC)]. However, tagging style checking tools like the JATS4R Validator extend beyond evaluating well formedness or structure and syntax to evaluating XML for sensibility.[11] That is testing it against specific best practices—in this case, those defined in JATS4R recommendations. These may be additional, more restrictive, structural or syntactical rules (see Fig. 1) or they may be content-specific rules (see Fig. 2). “Valid” in this context does mean that the article is flawless; the tool is useful to highlight areas where tagging and content might deviate from recommended practices.

Fig. 1 A restrictive structural or sytactical rule example.

15. <title>. JATS requires that <sec> (and similar elements taking <title> that also take <sec>, such as <abstract>, <ack>, and <app>) be properly nested. To create accessible headings, <title> must be included in each <sec>.

The JATS Journal Publishing section model requires either a <title> or <label> for each <sec>. The JATS Arching section model requires neither <title> nor <label>. To create accessible and article navigation in renderings or JATS XML that represents the article structure accurately, each section MUST have a title that can represent that section. Section tagging—titleless sections or sections with the @disp-level attribute different from the structural level of the section—is sometimes used to control the appearance of the content (specifically the headings) on paper (or PDF).

Fig. 2 A content-specific rule example.

20. @alt. Use to provide a short textual alternative or pronunciation guide for components such as abbreviations and emoticons—for example, to indicate that “WHO” should be pronounced “W.H.O.” or “World Health Organization”, and not “who”; or that “:-)” should be interpreted as “smile”

Example 14. Pronunciation

<p>According to the <abbrev alt="W.H.O.">WHO</abbrev>, regular exercise can help reduce the risk of noncommunicable diseases such as heart disease, stroke, and diabetes.</p>

Unlike the example in Box 1 that restricts the structure of the article further than the JATS schemas, this recommendation provides guidance on how to tag content to make it more accessible to screen readers by providing the pronunciation in the @alt attr

It is important to understand that the goal of using the validator is not to eliminate error messages. Simply resolving flagged issues without understanding their context or importance undermines the spirit and goals of JATS4R—to make the future corpus of articles more reusable and interchangeable. The validator is a tool to guide users in refining their XML, ensuring it aligns with community-driven standards while preserving the spirit of accessibility, interoperability, and usability.

### The Online JATS4R Validator

Fig. 3 The Validator home screen.

The online JATS4R Validator (https://jats4r.niso.org/jats4r-validator/) provides an interface for testing individual XML articles. The validation process involves several steps:

1. Upload: Users upload a single XML file to the tool.
  Fig. 4 The Validator file upload screen.
2. Initial checks: The validator assesses the file for well-formedness and validity against the DTD referenced in the DOCTYPE declaration. If errors are found, the validation halts, and the issues are reported.
  Fig. 5 The file is checked for well-formedness and validity before the recommendations are tested.
3. JATS4R Schematron testing: Once the file is confirmed to be well-formed and valid, it is tested against the JATS4R Schematron. This includes all JATS4R rules, with results categorized as ERROR or WARNING.
  Fig. 6 Schematron tests.
  Valid files are tested against the JATS4R Schematron. Errors and Warnings are listed on the right side. Clicking on these will take you to the appropriate place in the file.

### The JATS4R Schematron

The JATS4R Schematron (https://github.com/JATS4R/jats-schematrons) is available for download on GitHub. It provides the tests (based on the rules defined in the recommendations) that drive the validation process. The Schematron tests as many of the rules in the recommendation as possible, but some of the Recommendation Rules cannot be tested with Schematron (see Fig. 7).

Fig. 7 Not all rules can be tested with the Validator

19. @xml:lang. @xml:lang must be used to indicate the document language at the article level, and should then be used to indicate the language of any elements or phrases which differ from the main language used. Declaring the correct language of text affects the pronunciation used by screen readers. Follow JATS language code specifications.

Phrases which differ in language from their containing elements must be indicated using @xml:lang on <named-content> with the @content-type=”foreign-phrase” attribute (See Example 13).

This recommendation about setting the correct language on objects, phrases and the whole article is not tested with the JATS4R Validator. The default value set by the non-normative schemas and defined in the standard for @xml:lang on <article> is English, or "en". And the validator is not able to know if that is accurate or not.

Users can download the Schematron and run it locally and build it into their production workflows. This offers greater flexibility in rule selection and error reporting than using the Online Validator and does not require each article to be uploaded singly. The Schematron rules are organized into phases, allowing users to control the reporting level:

- Error Phase: Includes rules that flag critical issues—anything defined as a MUST in a recommendation.
- Warning Phase: Covers less critical but noteworthy issues—nything defined as a SHOULD in a recommendation.

Fig. 8 Phases for errors and warnings are defined in the root Schematron file (jats4r.sch)

<phase id="errors">
    <active pattern="abstract-errors"/>
    <active pattern="accessibility-errors"/>
    <active pattern="auths-aff-errors"/>
    …
</phase>
            
<phase id="warnings">
    <active pattern="abstract-warnings-1"/>
    <active pattern="abstract-warnings-2"/>
    <active pattern="accessibility-warnings"/>
    <active pattern="auths-aff-warnings"/>
    …
</phase>

Two Schematron files are created for each recommendation: one for errors ({recommendation}-errors.sch) and one for warnings ({recommendation}-warnings.sch). These are referenced by the main Schematron file, jats4r.sch, which coordinates the validation process.

Fig. 9 Recommendation-specific Schematron files are included by jats4r.sch.

These can be removed when running the tests locally.

… 
  <include href="accessibility-errors.sch"/>
  <include href="accessibility-warnings.sch"/>
            
  <include href="auths-affs-errors.sch"/>
  <include href="auths-affs-warnings.sch"/>
…

### The Validator Software

There are three GitHub repositories related to the validator.[13]

## Conclusions

It is our hope that these guidelines will help people meet updated accessibility requirements and make it easier to run content through the JATS4R Schematron. Approaching your workflow from the perspective of creating born-accessible content and keeping accessibility in mind through every stage of a document’s lifecycle should make it easier and more cost-effective to publish content that conforms to WCAG accessibility standards, USA’s Section 508, the 2025 European Accessibility Act, Canada’s Accessibility Requirements, Japanese Industrial Standards, and any other legislation that could prevent your content from being distributed in a global environment.

Using these tools and checklists can help your content reach a broader audience and potentially protect you from legal issues. Several markets will simply be unable to purchase content that does not meet these standards. Let’s all make our content as accessible as possible for as many people as possible, as early as possible.

## Conference Links

JATS-Con Home (https://jats.nlm.nih.gov/jats-con/)

Presentation Slides (https://jats.nlm.nih.gov/jats-con/2025/presentations/JATS4R_Accessibility_Applied.pptx)

## References

1 NISO Z39.96-2024 Journal Article Tag Suite (JATS) version 1.4. https://www.niso.org/publications/z3996-2024-jats
2 JATS non-normative supporting materials. https://jats.nlm.nih.gov
3 https://jats4r.niso.org/
4 Accessibility Recommendation. JATS for Reuse. 13 March, 2024. 10.3789/niso-rp-47-2024 (http://dx.doi.org/10.3789/niso-rp-47-2024) https://jats4r.niso.org/accessibility/
5 Beck J. Enemies, Frenemies, or Allies? The JATS Standing Committee and JATS4Reuse. In: Journal Article Tag Suite Conference (JATS-Con) Proceedings 2022 [Internet]. Bethesda (MD): National Center for Biotechnology Information (US); 2022. Available from: https://www.ncbi.nlm.nih.gov/books/NBK580673/
6 IT Accessibility Laws and Policies. Section508.gov. May 2024. https://www.section508.gov/manage/laws-and-policies/
7 European Commission. "European Accessibility Act." https://employment-social-affairs.ec.europa.eu/policies-and-activities/social-protection-social-inclusion/persons-disabilities/union-equality-strategy-rights-persons-disabilities-2021-2030/european-accessibility-act_en/
8 CAN/ASC - EN 301 549:2024 Accessibility requirements for ICT products and services. https://accessible.canada.ca/en-301-549-accessibility-requirements-ict-products-and-services-1
9 JIS X 8341 (Japan). https://adasitecompliance.com/legislation/jis-x-8341-japan/
10 Web Content Accessibility Guidelines (WCAG) 2.1 W3C Recommendation 12 December 2024. https://www.w3.org/TR/WCAG21/
11 Bauman, S. (2010). The 4 "Levels" of XML Rectitude. Presented as poster in Balisage: The Markup Conference 2010. Montreal, Canada. http://bauman.zapto.org/~syd/temp/XML_rectitude.pdf
12 Maloney, Chris, Alf Eaton and Jeff Beck. "A client-side JATS4R validator using Saxon-CE." Presented at Balisage: The Markup Conference 2015, Washington, DC, August 11 - 14, 2015. In Proceedings of Balisage: The Markup Conference 2015. Balisage Series on Markup Technologies, vol. 15 (2015). 10.4242/BalisageVol15.Beck01 (http://dx.doi.org/10.4242/BalisageVol15.Beck01).
13 https://github.com/JATS4R
14 https://github.com/Schematron/stf/tree/master/iso-schematron-xslt2
15 https://github.com/JATS4R/jats-dtds
16 https://github.com/JATS4R/jats-schematrons