# Accessible math at scale: how JATS and intelligent editing tools rise to the challenge

Pressure to produce journals faster and more cheaply while also complying with accessibility obligations poses a unique challenge for math notation. Especially as the European Accessibility Act and the U.S. Americans with Disabilities Act begin imposing new requirements in 2025 and 2026, publishers will need to meet their accessibility obligations with the math in their articles and do so without breaking the bank. This paper will lay out some of the challenges with producing quality, compliant math in a high-volume, fast-paced scholarly journal and explain how popular XML desktop tools, Schematron quality control, and JATS markup can best be used for optimal results with math markup. We also explain how, with JATS, both MathML and LaTeX math notation can be used together in the same workflow and how one publisher developed a novel math editing tool in oXygen Editor, specifically for use with JATS articles, through the help of ChatGPT.

MathML—mathematical markup language—is widely acknowledged in the accessibility community as a best practice for rendering math that can be interpreted by screen readers and other assistive tools [1], and so MathML is often a critical part of solutions to meet accessibility obligations such as those stated in the European Accessibility Act (EAA) and the U.S. Americans with Disabilities (ADA) Act. While publishers have already been using MathML for decades as part of their journal production and publishing processes, unfortunately there are inherent drawbacks to MathML in journal production that can add expense and create friction with authors and readers. Our aim in this paper is to advocate for the use of MathML while at the same time identifying areas where MathML can create inefficiencies and quality issues, especially in a high-volume journal workflow, and offer some recommendations for addressing the challenge we’ve identified.

One of the main problems with MathML for journal production is that the verbose markup is not practical to write or edit directly (see Fig. 1). MathML is typically captured as an export format from graphical editing tools like Microsoft Equation Editor or is converted from LaTeX markup. In such a workflow, MathML is then edited, and rendered downstream in production with a variety of tools that reinterpret and rerender the math, with potential for unwanted shifts in presentation and underlying coding each time the math is touched.

In a high-volume journal such as Optica Publishing Group’s Optics Express, which publishes around 50,000 pages of math-heavy content annually, manuscripts are submitted by a large and diverse author community with a variety of expectations about how their math will be treated. Some authors use—or some might say misuse—a graphical editor to prepare their math in the most expedient way possible and do not seem to care greatly about consistency or standard conventions. Other authors take painstaking efforts to set their math with precise attention to detail around spacing, positioning, etc., and are highly concerned if any shifts occur in their desired presentation at any time in the production process.

Fig. 1 Example of a simple equation expressed as both MathML and LaTeX.

In a typical XML production workflow such as used with Optics Express, attempting to preserve the integrity of the voluminous math throughout the conversion, revision, and rendering processes with a variety of different tools and vendor services can be extremely time-consuming and expensive, and when problems appear, can risk creating mistrust and disappointment among authors. For some authors, even minute shifts in spacing, say, or in the size of fences in math are not tolerated and create discord and extra effort to address at the author page-proof step. As mentioned, with such a workflow each touch of math in production becomes risky as it can create an unwanted change, either because the math is continually being reinterpreted by a visual editing tool or, when viewed in variable rendering environments, can prompt a person working with the math to make adjustments that seem correct in one tool but have unwanted effects downstream, for example, in a PDF rendering. See Fig. 2 for an example.

Fig. 2 Rendering in a popular WYSIWYG tool (left) and as direct MathML output in MathJax (right).

In a WYSIWYG tool there are often multiple ways to get math to appear a certain way, which can lead to unpredicatable results in the MathML output.

Given the challenges that seem inherent when working with MathML, how can we achieve better fidelity of math throughout the process, including for the final PDF and HTML outputs, and also meet our accessibility obligations? After working with MathML production for nearly 20 years, in 2019 Optica Publishing Group staff identified three goals that we believed, if met, would greatly increase efficiency and accuracy of math during journal production:

1. Authors, publishers, and vendors must see absolutely identical math displays, regardless of the tool provided or stage of production.
2. Editing or rerendering math must not rewrite or alter the original equation source in any way (except at the point a change is required).
3. From initial JATS conversion through final PDF and HTML output, the math must be checked against (and remain compliant with) the final rendering targets.

To meet our first and third goals, we standardized on MathJax [2] as our common rendering engine across the entire workflow. The MathJax JavaScript framework is not only an accurate interpreter of MathML. It provides an array of accessibility features including audio output and braille. To ensure that MathJax would be a reliable visual guide, we began requiring our vendors to ensure that 100% of the math they delivered was MathJax-compliant from the start. The second goal—protecting the underlying code—led us to a conclusion that we may have suspected was true all along but didn’t know how to address: MathML, although a requirement for accessibility and a convention we had built our processes around, was not the best choice for our production workflow.

After considering many angles, we opted to migrate our math production process to use LaTeX code instead of MathML. For those not familiar with LaTeX, it is a typesetting language and composition system that excels at rendering beautiful math. For editing, LaTeX seemed ideal to work with because, unlike MathML, LaTeX markup is concise enough to edit directly without the need of a WYSIWYG (graphical) interface to continually reinterpret and rewrite the code (see Fig. 1). It’s true that many WYSIWYG math tools produce quite accurate results, but the level of accuracy we were trying to preserve across tens of thousands of pages was much higher than what any tool in our experience could offer. Our migration to LaTeX math would also make it practical for us to transition our page-composition process away from proprietary tools to an open-source LaTeX engine, which saved cost and allowed us to do more with less reliance on external vendors.

The transition from MathML to LaTeX in our workflow took approximately 6 months and another 6 months of refinement before solidifying into an efficient process. Vendors had to retool for manuscript conversion. Staff used to working with MathML had to become fluent in LaTeX coding. Suitable processes for composing JATS XML with LaTeX had to be established and perfected. But after 12 months, our production time was significantly faster (we cut our time in author proofs by more than half), authors were happier with their page proofs, and requests for postpublication corrections for adjustments to math were reduced to almost nothing. Ultimately, because of the change in process, we were able to dispense entirely with having our vendors perform page-proof corrections and allow our in-house staff to correct final files as they were preparing materials for publishing, thus greatly reducing our overall production costs.

We began this paper by stating that MathML was the standard for meeting various accessibility obligations, so where does it leave us if we have migrated our workflow from MathML to LaTeX? Fortunately, we were still able to provide MathML realiably at the end of the process. MathJax renders LaTeX by reinterpreting it as MathML, so throughout the process we were essentially looking at the final MathML ouput all along. And we were able to capture MathJax’s MathML output and store it back in our JATS XML for reuse in EPUB and HTML while using the LaTeX for page composition. The JATS tagging convention for storing versions of math is simple. It involves using the <alternatives> element to hold the LaTeX, the MathML, and potentially a graphic representation as well:

Box 1

<alternatives>

<tex-math notation="LaTeX" version="MathJax">$$...$$</tex-math>

<mml:math display="block">...</mml:math>

<graphic.../>

</alternatives>

To help enforce proper use of <alternatives> and to preserve MathJax-compatible conventions throughout the production process, we introduced Schematron checks (XML-aware programmatic checks) as an invaluable part of our math workflow. The Schematron checks can be particularly important in cases where authors who use LaTeX develop their own macros. Since MathJax may not support such custom macros, Schematron can detect them and prompt production to use another approach that complies with MathJax requirements. And because our XML conversion vendors also used our Schematron, we were able to push quality control upstream in the workflow and avoid problems early on. The Schematron validation would run constantly in our oXygen Editor and enforce rules like these:

- LaTeX math must appear within a proper math environment (such as within dollar sign delimiters)
- MathML must have a @display attribute with value "block" when its parent is <disp-formula> and "inline" when its parent is <inline-formula>
- MathML must use only normative @mathvariant values
- MathML identifiers shouldn’t use Unicode Private Use Area characters

Before we finish with our use case and offer some lessons learned, we should return to an important challenge that we skipped over and explain how we overcame that challenge with the help of AI.

To realize our vision of working with math throughout the process in a uniform rendering tool, first we needed an equation editor that could read in LaTeX and continually display the results in MathJax. For those familiar with MathJax, that might seem like an elementary requirement to meet. However, our production workflow was tied to oXygen XML Editor desktop edition—a popular XML software suite with a large user base—and a suitable tool for oXygen did not exist. When we first transitioned to LaTeX, we had some success with a Java plug-in tool called JLaTeXMath [3] that could render LaTeX equations directly in oXygen Editor and allow editing of the underlying code. However, the tool had significant limitations in what LaTeX conventions were supported and it did not use MathJax for display.

The lack of a suitable option for math editing left us with a difficult decision. Either abandon the oXygen XML Editor software we’d invested so heavily in for the past 12 years, or create a new math-editing tool that met our needs within oXygen. After speaking with various vendors, including Wiris, the provider of the popular WYSIWYG editor MathType [4], we decided to create our own tool. The math editor we needed had to (1) render LaTeX equations reliably and completely in MathJax and (2) provide efficient and direct editing of the underlying LaTeX code.

To meet the first objective, rendering with MathJax, we set up an internal MathJax server that would receive LaTeX code from the manuscript and return an SVG image of the math in real time to the authoring interface. The interchange between the JATS manuscript and the MathJax server was achieved through CSS commands and special oXygen functions. The second task, providing a convenient but safe code editor, was trickier. We needed an editing window to pop up when a user clicked on the equation image for interacting with the code. Again we used special oXygen functions (this time in conjunction with JavaScript) for a solution, but to get the tool to work without bugs, we kept running into problems that stumped even seasoned Optica programmers. It was only after we turned to ChatGPT and performed a few hundred iterations with AI that we succeeded in creating a fully performant tool, a tool that now reliably and robustly serves a staff and vendor team of more than 25 people. We have made our solution available through GitHub [5] and provide an illustration of the tool in Fig. 3.

Fig. 3 Custom oXygen Editor math tool showing MathJax rendering and editing environment for the underlying code.

Image from S. Srivallapanondh et al. [6]. See Ref. [5] for details on the tool.

By leveraging LaTeX, MathJax, and JATS XML as described, we have been able to meet our obligations to provide MathML outputs that comply with the EAA and ADA requirements. We achieved significant production efficiency by standardizing all our math to human-readable and MathJax-compliant LaTeX that could be edited in a way that allowed us to preserve the underlying code throughout the process. With this workflow change, we not only significantly reduced staff processing; we also increased author satisfaction and reduced the costly author-proof correction cycles. While we realize that our approach is not the only effective way for publishers to meet their obligations with math in a high-volume journal workflow, we hope that our experience offers some useful insights. We’ll conclude with some recommendations:

1. Require your vendors to ensure that all math they supply is MathJax compliant from the start and that compliance is maintained throughout the process.
2. When math is copious in your publications, use LaTeX as the working production format, as LaTeX math is human readable, open source, and can flow into a LaTeX-based page layout system if desired.
3. Employ intelligent tools in conjunction with JATS or other markup as part of the math workflow; tools like Schematron can be configured easily to enforce rules you may have around math.
4. Consider custom development if off-the-shelf options limit productivity and accuracy.

We hope these insights inspire others to explore novel, pragmatic solutions for creating high-quality math content at scale without compromising on speed, accuracy, or regulatory compliance.

## References

1 https://kb.daisy.org/publishing/docs/html/mathml.html.
2 https://www.mathjax.org/.
3 https://github.com/opencollab/jlatexmath.
4 https://www.wiris.com/.
5 https://github.com/OpticaPublishingGroup/LaTeX-in-oXygen-Editor.
6 Srivallapanondh S. et al., Opt. Express 33, 2558 (2025), 10.1364/OE.542061 (http://dx.doi.org/10.1364/OE.542061)