# Naming content as requirements in standards―the Standards Norway approach

What are requirements? And why is everyone talking about them? Do I need this in my organisation as well? And how can I do this in NISO STS?

More and more standards customers and standards authors are asking for markup of requirements in standards, and Standards Development Organizations (SDOs) are struggling to find a solution that integrates seamlessly with NISO STS. Many initiatives are on the way, many discussions are being had, and still only a handful of SDOs are addressing this need to date.

As an independent consultant, I have worked with Standards Norway to clarify the business needs and to design a practical solution to service the needs of the Oil & Gas Industry that is now implemented in their instance of Fonto XML. This presentation will walk you through the business problem, how we've solved it and what challenges we faced (and are still facing).

## Conference Links

JATS-Con Home (http://jats.nlm.nih.gov/jats-con/)

Video of Presentation (https://jats.nlm.nih.gov/jats-con/2022/videos/jatscon22-stadler.mp4)