# Accessibility

An overview of accessibility in publishing and how the JATS family can support it.

## Conference Links

JATS-Con Home (http://jats.nlm.nih.gov/jats-con/)

Video of Presentation (https://jats.nlm.nih.gov/jats-con/2022/videos/jatscon22-perera.mp4)