# Using BITS for 10 Years and Counting

In 2011, CFA Institute was an experienced user of the green Journal Archiving tag set for scholarly journals, conference proceedings, and white papers. But when we made the decision to insource the production of our flagship organizational publication―a set of equation- and table-heavy curriculum textbooks that had to be reproduced in their entirety from scratch on an annual basis―we knew there was no way we could tag that content simply as a journal. We evaluated different book tag sets before adopting the NLM Book Tag Set Version 3.0.

More than 10 years out from that decision, many things have changed. XML tagging meant to support the production of print books has been repurposed and extended to a greater number of products in a variety of different formats. The structure and the content of the curriculum has become increasingly complex. The content management systems and associated workflows by which the content moves in and out of XML have exploded. Tag sets have been updated and modernized. Our commitment to and appreciation for single-source publishing workflows grows.

## Conference Links

JATS-Con Home (http://jats.nlm.nih.gov/jats-con/)

Video of Presentation (https://jats.nlm.nih.gov/jats-con/2022/videos/jatscon22-maisannes.mp4)