# Enemies, Frenemies, or Allies? The JATS Standing Committee and JATS4Reuse

What is the difference between the JATS Standing Committee and JATS4Reuse? Why are there two groups? Who should I pay attention to? What happens if they don't agree?

## Conference Links

JATS-Con Home (http://jats.nlm.nih.gov/jats-con/)

Presentation Slides (http://jats.nlm.nih.gov/jats-con/2022/presentations/jatscon22-beck.pptx)

Video of Presentation (https://jats.nlm.nih.gov/jats-con/2022/videos/jatscon22-beck.mp4)

## Acknowledgments

This work was supported by the Intramural Research Program of the National Library of Medicine, National Institutes of Health.