# An Unprecedented Pivot to the New Normal

A conference closing presentation on the future of JATS, the future of JATS-Con, Declarative Markup, and a homework assignment.

## Conference Links

JATS-Con Home (http://jats.nlm.nih.gov/jats-con/)

Presentation Slides (http://jats.nlm.nih.gov/jats-con/2021/presentations/jatsconclose21.pptx)

Video of Presentation (https://jats.nlm.nih.gov/jats-con/2021/videos/JC21-11.mp4)

## Acknowledgments

This work was supported by the Intramural Research Program of the National Library of Medicine, National Institutes of Health.