# Using Journal Article Tag Suite (JATS) XML for scholarly journal articles written in Korean

Korea is the fifth ranking country for number of PMC journals. As of September 2013, 75 journals from Korea are included in PMC. Starting in 2013, a variety of funding agencies to research and journal publications began to introduce open-access, full-text databases in the fields of medicine, science, social sciences, and humanities. In those databases, Journal Article Tag Suite (JATS) 1.0 will be used so that Korean articles can be easily manipulated as full text XML. It is necessary for editors or publishers to make full text XML files based on JATS 1.0. I would like to introduce and present the current situation of application of JATS 1.0 to academic journals, not only in English but also in Korean, including the current technology, training programs, and the policy of the Korean Government on open-access, full-text XML. This experience in Korea can be a model in constructing mother-language, open-access, full-text journal databases based on JATS 1.0. The usefulness of JATS is stressed in scholarly journal publications of all fields, not just medical, and the propagation of the published information in Korea.

## INTRODUCTION

PubMed Central (PMC) has been a survival platform for medical journals from Korea, since it is one path to being indexed in PubMed. During the past 10 years, the number of medical journals that have been indexed in Medline is few. When medical editors in Korea fail in applying to Medline, they cannot help but change the language of their journals to English, and apply to PMC. For medical journals in English, if the XML quality level fits PMC’s required criteria, it is easy to be included in PMC. Since PMC sends the citation data of PMC journals to PubMed, the medical editors are very satisfied with PMC’s policy. Fig. 1 shows the number of journals included in PMC from 2008 to the present year. Owing to increased visibility via PubMed and PMC, a variety of medical journals from Korea became internationalized: first, they have been indexed in international citation databases such as Web of Science or SCOPUS; second, there has been an increased number of submissions from outside of Korea; and third, value of journal metrics has increased year by year. When the first training for PMC XML production was opened in 2006, we could not imagine this kind of promotion of medical journals from Korea [1]. The Korean Association of Medical Journal Editors (KAMJE) has played a major role in producing PMC XML files after constructing a full text database based on PMC XML, entitled KoreaMed Synapse, in 2007 [2]. Scholarly journal editors in other fields began to pay attention to the activities of KAMJE. KAMJE’s work gave scientists in Korea the initiative to organize the Korean Council of Science Editors (KCSE). KCSE launched in September, 2011. KCSE’s main works are education and training for science editors on the international level in editing, publication ethics, and publication of newsletters and journals. KCSE deals with a variety of editorial fields, including adaptation of information technology. In addition to scienctific fields, social science and humanities editors have a concern in the full-text, XML-based, open-access database that was supported by the National Research Foundation of Korea. Korea Centers for Disease Control and Prevention also began to construct KoreaPMC, like CanadaPMC or EuropePMC, this year, as the project of the National Library of Medicine of the Republic of Korea. The Korean Federation of Science and Technology Societies (KOFST) is also testing an XML-based, full-text, free or open-access database. In this presentation, we would like to introduce not only the Journal Article Tag Suite (JATS) XML-based, full-text databases in Korea but also the technology, training programs, and the policy of the Korean Government on open-access, full-text, XML-based databases.

Fig. 1 Number of PubMed Central journals from Korea according to year

## KoreaPMC

The foundation of KoreaPMC was first proposed by KAMJE. In March 2007, KAMJE discussed the idea with NCBI on the AGREEMENT FOR PARTICIPATION IN NIH PUBMED CENTRAL (NIH Portfolio) ARCHIVE. However, it was terminated in July 2007, since new policy on PMC international (PMCi) was introduced: first, PMCi should be supported by the local Government; second, there should be a public access policy on biomedical papers supported by the Government. Since not only is KAMJE not a Government supported organization, but also the Korean Government did not have a public access policy at that time, it was impossible for KAMJE to proceed with the project. In 2011, the Korean Government decided to make a new institute, the National Library of Medicine (NLM) of the Republic of Korea, under the Korea Centers for Disease Control and Prevention. The building began construction in 2012 and will be finished in 2013. As one of the database services of Korea NLM, KoreaPMC is also under construction. Owing to technical support from United States PMC, it is already well-established and in the testing period. KoreaPMC is going to receive non-Roman character papers, like papers in Korean. This project is completely supported by the Korean Government. KoreaPMC can be also accepted as the third PMCi by PMC, since the Minister of Health and Welfare declared the open access policy for the papers supported by the Ministry in 2012. KoreaPMC may appear at the end of 2013 or early 2014.

## Social Science and Humanity Central

In August 2013, the National Research Foundation (NRF) of Korea selected a company to maintain the Korean Citation Index (KCI) system, which is the citation database of 2,000 scholarly journals in Korea including science, technology, engineering, medicine, social science, and humanities & arts, similar to Web of Science or SCOPUS. NRF of Korea also asked the company to establish Social Science and Humanity Central (SSHC) for scholarly journals in Korea. Journals in English in the fields of social science and humanities will be selected and a JATS XML-based, full-text, open-access database, of which the number of papers is currently 1,000, will be shown like PMC in early 2014. There had been no international citation full-text, open-access database in the fields of social science and humanities in the world. SSHC will be the first step in this direction. SSHC will imitate PMC since it is the well-established model of full-text, free or open-access literature archives; however, it will accept any local or regional language journals in the world. This work is possible according to the announcement of the Ministry of Education that stressed open access policy for support of scholarly journal publication in December 2011. Through SSHC, the visibility of journals from Korea may increase dramatically. Korea and Japan are two unique countries out of 34 OECD ones that have supported scholarly journal publication. The Korean Government supported 8 million US dollars in 2013; meanwhile, the Japanese Government supported 5 million US dollars in 2013. The Korean Government wants scholarly journals to be competitive in addition to the papers of researchers. Also the Government wants to increase the knowledge of general people by providing contents freely. It is the reason why the Korean Government supports scholarly journal publication and full text databases.

## ScienceCentral

ScienceCentral is a free or open-access, full-text archive of scientific society journal literature at KOFST. It is in testing with eight journals from Korea and one from Croatia as of September 2013 [3]. Out of eight journals, two are in Korean. The Korean Government has supported scientific, technological and medical journals through KOFST and social science, humanities & arts journals through NRF of Korea. KOFST has three separate supporting systems: first for national journals; second for international journals, usually in English; third, tailored journal support including: consulting or payment for masthead; instruction to authors; publication ethics training; style and format development; design of cover page; layout of text pages; journal policy development; manuscript editing; English proofreading; a manuscript management system; a journal homepage; production of JATS XML and CrossRef XML; realization of ORCID, CrossMark, and Fundref; and regular training for editors or editorial board members. After a long experience of journal support, KOFST comprehended that a full-text, open-access platform like PMC is necessary for scholarly journals from Korea to broaden visibility; therefore, it decided to construct ScienceCentral, a clone of PMC in the field of science. The three prominent differences from PMC are as follows: first, it includes all scientific fields including technology, engineering, life science and multi-disciplinary science; second, it includes journals in all languages in the world if the abstract, tables, figures, and references are also provided in English; third, it accepts only society or non-profit institutional journals [4]. It is a new experiment in full-text, open-access databases. It is still uncertain what number of open-access, non-profit, society or institutional journals will participate in ScienceCentral. Since the cost of JATS XML production is very reasonable nowadays, there will not be so much burden to publishers. KOFST can provide full cost of JATS XML production for scientific journals from Korea. KOFST has a plan to support the JATS XML production for journals from the world through an official development assistance (ODA) program. The ODA program may help journals from developing countries to be positioned in the high-quality, full-text database. Another purpose of ScienceCentral is to help local or regional languages to survive in scientific writing. It is well-known that the language of science is English; however, if the full text of other languages is presented in JATS XML format, and translated into other mother languages according to technical development, those languages can survive as a tool of propagating scientific information for human beings.

## How to show Korean or other language characters via JATS XML

Korean authors usually write papers in English for international readers; however, to submit Korean language journals for local readers, they write in Korean. In 2012, JATS became a standard journal eXtensible Markup Language (XML) through NISO. The most prominent advantage of JATS DTD is that it can accept all languages in the world if it can be encoded in Unicode Transformation Format (UTF)-8. There was no specific technical or economic challenge to archives for Korean-language content, owing to the JATS DTD. The implementation of JATS in Korean language publications is very simple since there is language code schema in JATS DTD. It provides a variety of languages besides Korean very easily by adding the language attribute, “xml:lang Language.” For example, the following article declaration can present Korean characters.

<article
   article-type="research-article"
   dtd-version="1.0" 
   xml:lang="ko"
   xmlns:mml="http://www.w3.org/1998/Math/MathML"
   xmlns:xlink="http://www.w3.org/1999/xlink">

If any languages are substituted, the language code can be changed: xml:lang="ja-Hani" (Japanese written in Kanji (Hanzi, Hanja, Han)), “mn” (Mongolian), “war” (Philippines), “vi” (Vietnamese), “zh” (Chinese), and “cs” (Czech). Also the language code can be inserted in many part of JATS XML to present multiple specific languages. DOIs for Korean-language references can also be seen without difficulties when transformed from JATS XML to CrossRef XML.

## Training programs for JATS XML

In August 2006 there was the first seminar for PMC XML production organized by Dr. Sun Huh (former Chair of the Committee on Information Management, KAMJE) [4]. After that, KAMJE staff could produce PMC XML. Since there was a remarkable increase of tags between PMC XML and JATS XML, it is necessary to train the editors, manuscript editors, staffs of societies, and staffs of printing or information technology companies. KCSE initiated the workshop with a topic “Application of information technology to scholarly open access journal publication” from July 4 to 5, 2013 at the KOFST building, Seoul. The number of registrations was 102, and the number of participants was 95. At the end of the workshop, 55 participants kept their seats. Three lecturers were from universities; two, from information technology companies; two, from manuscript editing companies; and one, from a university hospital library. The sessions and titles of each class for two days were as followings:

Box 1

#### Session 1: Journal XML

- 1. Journal Article Tag Set 1.0: New ISO standard of journal XML
- 2. How to make a full text XML of journal papers in English as well as in Korean based on JATS 1.0
- 3. JATS 1.0 XML coding
- 4. How to construct XSL and/or CSS for style sheet of XML files based on the data type definition
- 5. Showing HTML files from JATS XML files in the web

#### Session 2: Crossref XML

- 6. Basics of Crossref XML
- 7. Crossref XML coding
- 8. How to convert the JATS 1.0 XML to Crossref XML
- 9. How to add hyperlink and cited-by function using DOI
- 10. How to apply ORCID, FundRef via Crossref XML
- 11. How to apply CrossMark

#### Session 3: Network and viewer tools

- 12. Adoption of social network service, and QR code
- 13. Pubreader: New tool of journal paper reader convenient to web, smart pad, and phone environment
- 14. How to install homepage of the journal to smart phone app, and smart pad app
- 15. N-Screen for access from a variety of device environment with one source applicable to scholarly journal

The purpose of this workshop is to promote each journal’s international competitiveness. Of course, the most important point is the high quality content of papers; however, most high quality papers swim toward high impact-factor journals. Therefore, the local journals published by scholarly societies have a difficulty in receiving the best quality papers. Although the content itself is not the best, the visibility can be increased if the journal homepage is good and/or the journal is indexed in international open-access databases. For increased visibility, JATS XML is the basic step. From JATS XML, other XML formats can be transformed very easily and can be integrated by viewers such as Pubreader. The best example is KoreaMed Synapse [2]. To increase international visibility, 142 medical editors from Korea participated in KoreaMed Synapse, a digital archiving and reference linking platform of Korean medical journals. It produces full text JATS XML for English papers, as well as abstract and reference XML for Korean papers.

To construct a full-text, open-access journal homepage or database, the understanding of JATS XML is essential for editors. If the journal is published by international commercial companies, editors do not need to learn those complicated technologies. However, most scholarly journals are published by societies, and they should understand the advancement of information technology applicable to their journals. If editors understand how to produce JATS XML and how to use JATS XML for other XMLs or viewers, they will be able to have confidence to apply those technologies to their journals. It was possible since editors have a very high level information technology background as is common among Koreans. They understood the content well and practiced the XML coding and conversion without difficulties with their own laptop. They confirmed that most items such as CrossRef XML, cited-by function through DOI, ORCID, CrossMark, and Fundref XMLs are easily obtained from JATS XML. They saw how QR codes worked and what the merits are of journal apps. Pubreader was a fantastic topic for editors since it is the one of tools for N-screen. N-Screen means user-centered service, where the user co-owns and executes multiple applications at anytime, anywhere, without interruption through an advanced smart system. The linking service among devices such as smart TV, smart phone, smart pad, laptop, and audio device are standardized according to the advancement of a variety of smart devices and cloud services. When editors understand those kinds of new standards or XML techniques, they can ask engineers more easily to realize those services. It is also for better understanding of information terminologies used in journals.

## Is it mandatory for scholarly societies to publish journals as open access if they receive the Government’s funds in Korea?

No, KoreaPMC is not based on an open-access journal policy, but an open-access paper policy when results are supported by the Government. No, SSHC is still a preliminary project so it is not mandatory to submit JATS XML-based full text to NRF of Korea. Not yet, but as for ScienceCentral, KOFST has a more powerful policy, it has a plan to give a favor to journals of which JATS XML files are submitted to KOFST to deposit to ScienceCentral from 2015. Since KOFST supports scholarly journals, it is possible to add ‘JATS XML’ item in the evaluation items of journals. After that, most editors do their best to fulfill the items recommended by KOFST to get the funds. It may be the first case of open access journal policy by the Government. Up to the end of 2014, the deposit of JATS XML files to ScienceCentral will be optional.

## CONCLUSION

The purpose of this presentation is to introduce the Journal Article Tag Suite (JATS) XML-based, full-text databases in Korea; and the technology, training programs, and the policy of the Korean Government on open-access, full-text, XML-based databases. Readers may be able to understand why there is an appearance of such databases and the background of those phenomena through the description. Also, the training program for editors may be helpful to other countries or other fields. It will be interesting to trace if three kinds of databases, KoreaPMC, SSHC, and ScienceCentral persist continuously and prosper by participation of many open access journal publishers.

## Acknowledgments

Conflict of Interests

No potential conflict of interest relevant to this article was reported

Acknowledgments

This work is supported by the Research Grant of the National Research Foundation of Korea (policy research-2013-003-academic infrastructure promotion) and the Korean Federation of Science and Technology Societies (2013), Government of the Republic of Korea.

## References

1 KoreaMed technical workshop, 2006 [Internet]. Seoul (KR): the Korean Association of Medical Journal Editors. 2006. [cited 2013 Sep 16]. Available from: http://kamje.or.kr/workshop/2006/0811/1.pdf.
2 KoreaMed Synapse [Internet]. Seoul (KR): the Korean Association of Medical Journal Editors. 2013. [cited 2013 Sep 16]. Available from: http://synapse.koreamed.org/.
3 ScienceCentral [Internet]. Seoul (KR): Korean Federation of Science and Technology Societies. 2013. [cited 2013 Sep 16]. Available from: http://e-sciencecentral.org/.
4 Huh S. ScienceCentral: open access full-text archive of scientific journals based on Journal Article Tag Suite regardless of their languages. Biochem Med. 2013;23:235-236. 10.11613/BM.2013.029.