# Ontology based Biomedical Research Paper Authoring Support Tool

Biomedical research papers typically formatted as IMRAD structure: Introduction, Methods, Results, and Discussion. Even though following this format, writing a paper in English is challenging for authors, because the most difficult thing is to organize and present their ideas with appropriate expressions.

Our goal is to develop a paper authoring support system that helps biomedical scientists to organize their ideas for a specific discourse purpose. As an initial step toward the goal, this study developed an abstract authoring support tool that provides candidate lexical bundles organized according to IMRAD structure. Lexical bundles function as basic building blocks of this discourse structure. For example, the lexical bundle ‘the purpose of this study was’ indicates the research purpose in the Introduction section. Lexical bundles were extracted from sentences in 152,083 structured abstracts of the PubMed Central Open Access Subset and analyzed their distribution by IMRAD sections. To organize lexical bundles according to IMRAD, the Lexical Bundle Ontology was built. Then, a JATS-compliant authoring support tool was implemented. This tool lists up candidate lexical bundles responding to authors' discourse purposes in a specific section and thereby helps to complete sentences. We present a use case scenario of this authoring support tool. We expect that this tool be a useful, at least in biomedical abstract writing, to organize author’s ideas to achieve specific discourse purpose. This tool is target to primarily for biomedical scientists whose mother tongue is not English. However, native speakers may still find the utility.

## Introduction

Biomedical research papers typically formatted as IMRAD structure: Introduction, Methods, Results, and Discussion. Even though following this format, writing a paper in English is challenging for authors because the most difficult thing is to organize and present their ideas with appropriate expressions. This is roughly true for all authors, regardless of their mother tongue is English or not.

Our goal is to develop a paper authoring support system that helps biomedical scientists to organize their ideas for a specific discourse purpose. As an initial step toward the goal, this study developed an abstract authoring support tool that provides candidate lexical bundles organized according to IMRAD structure. Lexical bundles function as basic building blocks of this discourse structure. For example, the lexical bundle "the purpose of this study was" indicates the research purpose in the Introduction section.

The motivation for this study arises from the fact that each IMRAD section has highly codified discourse purpose and have frequently occurring lexical bundles. Our approach also draws on the literature that has found out: i) communicative meanings and functions are often realized by formulaic expression (1); ii) complying with IMRAD format, academic authors adopt predetermined phraseological patterns in discourse steps (2).

The rest of this paper is organized as follows. Background section overviews previous works on lexical bundles in the biomedical domain. Method section describes the how we collect lexical bundles, and develop an ontology and abstract authoring tool. Result section provides the authoring tool interface and its use case scenario. Finally, we discuss and conclude the study.

## Background

A study showed more compact set of vocabularies are used in biomedical science texts compared to general English (3). In the roughly same line, Wang, Liang and Ge (4) compiled the Medical Academic Word List, which is a list of the most frequently used medical academic words in medical research papers. However, individual word forms are not enough because most rhetorical functions are not accomplished by a word list.

Lexical bundles are combinations of three or more words that frequently occur in a corpus (5). They have many names: ‘n-grams’, ‘multi-word patterns’, ‘formulaic patterns’, ‘clusters’, or ‘collocation’. Though they are not complete structural units, lexical bundles work as basic building blocks of discourse. Several researchers focused on characterizing lexical bundles in the research article. Cortes (6) analyzed the relationship of the lexical bundles to the ‘moves’ in the introduction section of research article. He identified that some lexical bundles made of more than five words triggers the communicative function of a move (i.e.,‘the purpose of this study was’ describe the objective of study). Saber (2) analyzed the differential distribution of lexical bundles in the different IMRAD sections in biomedical research articles and found a limited repertoire of key standardized phraseological patterns specific to certain rhetorical steps. Ron Daniel (7) demonstrates that lexical bundles work as clear signal of discourse purpose in abstract text. Lorenzo Salazar (8) investigated the frequency, structure, and functions of lexical bundles in English research paper.

In sum, previous studies have demonstrated the utility of lexical bundles as a good tool to achieve specific discourse purpose. A formulaic expression compendium (9) is an another evidence for the utility. Drawing on the utility of lexical bundles, we developed an abstract writing support tool that helps to combine the right lexical bundles with the right discourse step.

## Methods

### Data Source

To collect lexical bundles for authoring support tool, we identified the salient lexical bundles in a specific IMRAD section. The data source for lexical bundles is the structured abstracts of research articles (n=152,083) in the PubMed Central Open Access Subset (10).We repurposed the data collected for our another project (11). Thus, the data processing steps in this study are partially same with those in (11).

### Extraction of lexical bundles

#### Section grouping and sentence splitting

Our structured abstract corpus have very diverse section headings (n=1,628). This variants come from plurals (Conclusion, Conclusions), modifier (Conclusion, Major Conclusion), different word sequence (Conclusions and Significance, Significance and Conclusion), and joint section headings (Method and Result, Result and Discussion) (12). Different section headings of the same concept were merged into 1,001 headings using OpenRefine (13), then further normalized into IMRAD using the NLM’s category mapping table ((14)). The mapping table uses five categories: Background, Objective, Methods, Results, and Conclusions. In our study Background and Objective were merged into Introduction and Conclusions was renamed to Discussion. To extract lexical bundles, LingPipe (15) was used for sentence splitting. Each sentence was appended by corresponding IMRAD heading.

#### Analysis of lexical bundles

After grouping sections into IMRAD, lexical bundles were extracted from sentences in each section, and then their occurrence frequency was analyzed using our in-house program. The lexical bundles under 50 of occurrence frequency were ignored. The lexical bundles in this study are defined as: all n-grams (from 2 to 10-gram) without any further processing except numbers, which were marked with special tag, NUM. (Table 1) shows that each IMRAD section has often occurring lexical bundles.

Table 1

Table 1. Distribution of the top-3 lexical bundles in the IMRAD section of PMC OA subset (from 3-gram to 10-gram bundles)

Introduction | Freq. | Methods | Freq. | Results | Freq. | Discussion | Freq.
of the | 130,996 | of the | 63,454 | NUM % | 480,724 | of the | 94,020
in the | 94,588 | and NUM | 61,634 | NUM NUM | 294,308 | in the | 79,248
of this | 45,916 | NUM NUM | 55,754 | of the | 191,242 | to the | 32,302
study was to | 31,444 | n = NUM | 25,918 | NUM NUM % | 101,998 | as well as | 8,192
of this study | 29,622 | NUM and NUM | 21,810 | NUM ± NUM | 58,342 | results suggest that | 7,828
this study was | 23,354 | was used to | 12,098 | NUM % of | 56,900 | in patients with | 7,182
of this study was | 22,792 | A total of NUM | 6,004 | NUM % CI NUM | 47,016 | These results suggest that | 2,818
this study was to | 22,518 | between NUM and NUM | 4,764 | NUM NUM % CI | 39,362 | Our results suggest that | 2,670
The aim of this | 15,124 | NUM mg / kg | 4,460 | % CI NUM NUM | 32,358 | can be used to | 2,524
of this study was to | 22,346 | were divided into NUM groups | 2,002 | NUM NUM % CI NUM | 32,792 | The results of this study | 1,382
The aim of this study | 12,788 | A total of NUM patients | 1,340 | NUM % CI NUM NUM | 32,302 | play an important role in | 1,048
aim of this study was | 11,530 | were included in the study | 1,302 | NUM % and NUM % | 17,240 | for the first time that | 830
aim of this study was to | 11,286 | mean age NUM ± NUM years | 702 | NUM NUM % CI NUM NUM | 24,766 | our knowledge this is the first | 774
The aim of this study was | 10,796 | A total of NUM patients with | 506 | = NUM NUM % CI NUM | 8,602 | To our knowledge this is the | 494
purpose of this study was to | 5,870 | were randomly divided into NUM groups | 500 | OR NUM NUM % CI NUM | 8,126 | To the best of our knowledge | 442
The aim of this study was to | 10,560 | were divided into NUM groups according to | 282 | = NUM NUM % CI NUM NUM | 6,924 | To our knowledge this is the first | 472
The purpose of this study was to | 5,558 | NUM / NUM and NUM / NUM | 200 | OR NUM NUM % CI NUM NUM | 6,220 | To the best of our knowledge this | 342
The objective of this study was to | 3,642 | ratios ORs and NUM % confidence intervals | 180 | NUM NUM % CI NUM to NUM | 5,190 | the best of our knowledge this is | 314
The aim of the present study was to | 1,896 | ratios ORs and NUM % confidence intervals CIs | 142 | OR = NUM NUM % CI NUM NUM | 4,050 | To the best of our knowledge this is | 304
The aim of this study was to investigate | 1,758 | odds ratios ORs and NUM % confidence intervals | 126 | = NUM NUM % CI = NUM NUM | 3,478 | the best of our knowledge this is the | 300
The aim of this study was to evaluate | 1,660 | were divided into NUM groups according to the | 120 | OR = NUM NUM % CI = NUM | 2,916 | best of our knowledge this is the first | 286
The aim of this study was to evaluate the | 1,200 | odds ratios ORs and NUM % confidence intervals CIs | 102 | OR = NUM NUM % CI = NUM NUM | 2,396 | To the best of our knowledge this is the | 292
The aim of this study was to investigate the | 1,126 | with a mean age of NUM ± NUM years | 96 | NUM NUM % CI NUM NUM p = NUM | 1,922 | the best of our knowledge this is the first | 284
The aim of this study was to determine the | 820 | odds ratios OR and NUM % confidence intervals CI | 82 | NUM % NUM % NUM % and NUM % | 1,418 | best of our knowledge this is the first report | 88
The aim of the present study was to investigate the | 246 | / NUM / NUM and NUM / NUM / NUM | 70 | NUM NUM % confidence interval [ CI ] NUM NUM | 890 | To the best of our knowledge this is the first | 276
The aim of the present study was to evaluate the | 224 | NUM / NUM / NUM and NUM / NUM / | 70 | NUM % NUM % NUM % and NUM % respectively | 744 | the best of our knowledge this is the first report | 86
aim of this study was to evaluate the effect of | 142 | between NUM / NUM / NUM and NUM / NUM | 62 | NUM % NUM % CI NUM % to NUM % | 626 | the best of our knowledge this is the first case | 60

### Lexical Bundle Ontology

We designed a simple ontology, Lexical Bundle Ontology (LBO) that organizes lexical bundles according to IMRAD. Thus, LBO extends the generic IMRAD model to induce its own classes. LBO has four classes under the top class LexicalBundle: IntroductionBundle, MethodBundle, ResultBundle, and DiscussionBundle. Each class has three owl:Datatype Properties: frequency, nGram, and rdfs:label. The prefix ‘lbo’ was declared for the dereferenceable URI (http://lbo.studiosusan.kr/), where an application can find and access to bundle instances. The box below shows a LBO instance in Turtle. The 9-gram lexical bundle (‘The aim of the present study was to evaluate’) is identified by ‘IntroLBl1108’ and its frequency is 326.

Box 1

				:IntroLbl1108
				a       :IntroductionBundle ;
				rdfs:label "The aim of the present study was to evaluate" ;
				:frequency 326 ;
				:nGram  9 .

### Implementation of Authoring Support Tool

A JATS-compliant authoring support tool prototype was implemented. This proof of concept tool was designed to list up candidate lexical bundles responding to a writer's discourse purpose and thereby help to complete sentences in abstract. The Apache Lucene library was used for indexing and searching the lexical bundles in LBO. To recommend lexical bundles for a specific discourse purpose, they can be sorted by occurrence frequency, length of n-gram, or alphabetical code order. In our tool the bundles are sorted by their occurrence frequency.

A user completes a sentence by juxtaposing the last words of a given bundle with the first words of other bundles available to come. To make it happen, the left token-first-partial matching method was applied. When a user types a string, the tool in real-time matches bundles from the index file and return the matched items to the user. For the interactive user interface AJAX was used.

## Results

When a user writes an abstract according to the IMRAD format, the tool lists up candidate—up to ten—lexical bundles (Fig. 1). The tool is case-sensitive. When a user enters an upper case letter at the very beginning of a string, the tool returns all bundles beginning with the typed letter. The completed texts are transformed to JATS format by clicking the button: Convert to JATS format. The Paper Authoring Support Tool is available from http://147.46.166.180:7000/jats/demo.html at the time of writing.

Fig. 1

Fig. 1.Prototype Interface of the Biomedical Research Paper Authoring Support Tool.

### Use-case Scenario

In this section, we present a use-case scenario to show the utility of the tool for authors. Let us we show writing an abstract of a published paper (16) with this tool.

In the introduction section, the author begins with describing background knowledge and presenting the knowledge gap with the lexical bundle ‘However little is known about’ (Fig. 2). Then she states research purpose with an expression such as ‘In this study we investigated the’ (Fig. 3). Methods section often involves describing a study type (Fig. 4)4, subject (Fig. 5), and experimental procedure (Fig. 6). Results section often has statistical test results (Fig. 7) with confidence interval (Fig. 8). The discussion section often completes with an expression such as ‘Our results indicate that’ (Fig. 9). In each step of writing, the author selects a proper bundle serving her discourse purpose. Finally by clicking the button the author transform the text to the JATS XML format.

Fig. 2

Fig. 2. Use-case of the Biomedical Research Paper Authoring Support Tool (1).

Fig. 3

Fig. 3. Use-case of the Biomedical Research Paper Authoring Support Tool (2).

Fig. 4

Fig. 4. Use-case of the Biomedical Research Paper Authoring Support Tool (3).

Fig. 5

Fig. 5. Use-case of the Biomedical Research Paper Authoring Support Tool (4).

Fig. 6

Fig. 6. Use-case of the Biomedical Research Paper Authoring Support Tool (5).

Fig. 7

Fig. 7. Use-case of the Biomedical Research Paper Authoring Support Tool (6).

Fig. 8

Fig. 8. PUse-case of the Biomedical Research Paper Authoring Support Tool (7).

Fig. 9

Fig. 9. Use-case of the Biomedical Research Paper Authoring Support Tool (8).

## Discussion

This study presented an abstract authoring support tool which lists up candidate lexical bundles responding to authors' discourse purposes in a specific IMRAD section and helps to complete sentences. We hope the use case scenario have demonstrated the viability of this proof of concept tool.

The implications of the tool are obvious. It would be a useful tool, at least in abstract writing, to organize author’s ideas to achieve specific discourse purpose. Thereby it would generate a well-organized and clearly written manuscript. This tool is target to primarily for biomedical scientists whose mother tongue is not English. But, native speakers may still find the utility. This tool also can be useful for authors in any other scientific domain because many lexical bundles are commonly used in scientific paper.

Admittedly this exploratory study extracted the lexical bundles from the abstracts in the PMC OA subset, thus it does not show the all thematic contents in the bodies of research papers. Further studies are required to cover full text papers. Further work includes refining the authoring support tool. The grouping the lexical bundles with a similar role into a single group is a way to go (e.g., the two lexical bundles ‘the objective of this study’ and ‘the aim of this study’ have a similar role). This semantic structurewill help highly selective searching for lexical bundles.

In conclusion, we hope that the present work will promote JATS community to start discussions on and endorsement of this authoring support tool.

## Acknowledgments

Competing interests

The authors declare that they have no competing interests.

Acknowledgments

This research was supported by Basic Science Research Program through the National Research Foundation of Korea (NRF) funded by the Ministry of Education, Science and by a grant from the Korea National Institute of Health intramural research (No. 4800-4848-307 and No. 3000-3334-300).

## References

1 Martinez R, Schmitt N. A Phrasal Expressions List. Applied Linguistics. 2012;33(3):299-320. http://dx.doi.org/10.1093/applin/ams010.
2 Saber A. Phraseological patterns in a large corpus of biomedical articles. In: Boulton A, Carter-Thomas S, Rowley-Jolivet E, editors. Corpus-Informed Research and Learning in ESP: Issues and applications. Amsterdam. John Benjamins Publishing Company. 2012:45-82.
3 Waxmonsky S, Goldsmith J, Rzhetsky A, editors. Discovering and Counting Biomedical Verbs. 2010 Ninth International Conference on Machine Learning and Applications. 2010: IEEE.
4 Wang J, Liang S-l, Ge G-c. Establishment of a Medical Academic Word List. English for Specific Purposes. 2008;27(4):442-58. http://dx.doi.org/10.1016/j.esp.2008.05.003.
5 Biber D, Conrad S, Cortes V. If you look at …: Lexical Bundles in University Teaching and Textbooks. English for Specific Purposes. 2004;25(3):371-405. http://dx.doi.org/10.1093/applin/25.3.371.
6 Cortes V. The purpose of this study is to: Connecting lexical bundles and moves in research article introductions. Journal of English for Academic Purposes. 2013;12(1):33-43. http://dx.doi.org/10.1016/j.jeap.2012.11.002.
7 Ron Daniel J. Domain-Independent Mining of Abstracts Using Indicator Phrases. D-Lib Magazine. 2012;18(7/8). http://dx.doi.org/10.1045/july2012-daniel.
8 Lorenzo Salazar DJ. Lexical bundles in scientific English: A corpus-based study of native and non-native writing: Universitat de Barcelona; 2011.
9 Morley J. Academic Phrasebank [updated June 21, 2013; cited 2013 April 6]. Available from: http://www.phrasebank.manchester.ac.kr.
10 NLM. PMC FTP Service: US National Library of Medicine; [cited 2011 April 12]. Available from: http://www.ncbi.nlm.nih.gov/pmc/tools/ftp/.
11 Nam S, Jeong S, Kim H-G. Lexical feature driven sentence classification for biomedical paper abstracts. [Journal Article Manuscript]. In press 2013.
12 Ripple AM, Mork JG, Rozier JM, Knecht LS. Structured Abstracts in MEDLINE: Twenty-Five Years Later2012. Available from: http://structuredabstracts.nlm.nih.gov/Structured_Abstracts_in_MEDLINE_Twenty-Years_Later.pdf.
13 OpenRefine. 2012
14 NLM. Structured Abstracts in MEDLINE: Implementation Information 2012 [cited 2012 September, 22]. Available from: http://structuredabstracts.nlm.nih.gov/Implementation.shtml.
15 Smith L, Rindflesch T, Wilber T. MedPost: a part-of-speech tagger for bioMedical text. Bioinformatics. 2004;20(14):2320-1.
16 Kim M-J, Lim N-K, Park H-Y. Relationship between prehypertension and chronic kidney disease in middle-aged people in Korea: the Korean genome and epidemiology study. BMC Public Health. 2012;12(1):960. PubMed PMID: http://dx.doi.org/10.1186/1471-2458-12-960.