# Beware! The Spork

Advice, advice, advice. There is so much advice on how to use the JATS. And everyone seems to have an opinion about how you should deal with your content.

## Conference Links

JATS-Con Home (http://jats.nlm.nih.gov/jats-con/)

Presentation Slides, PowerPoint (http://jats.nlm.nih.gov/jats-con/program/2012/presentations/beck_jatscon2012.zip)

Video of Presentation (http://videocast.nih.gov/summary.asp?Live=11979&start=18762)