# Best Practices or Common Practice?

The JATS is pretty big. And there is some documentation — and some examples. But when you come across a tagging question, the easiest thing to do is to solve it like someone else solved it. You want to know how THEY do it over there, or how THAT GUY who wrote this software that we use does it. Not all Practices are "Best Practices", and even if they are they might not be right for you.

## Conference Links

JATS-Con Home (http://jats.nlm.nih.gov/jats-con/)

Presentation Slides, PowerPoint (http://jats.nlm.nih.gov/jats-con/program/2011/presentations/beck.pptx)

Video of Presentation (http://videocast.nih.gov/summary.asp?Live=10573&start=443)