# Are We There Yet? An introduction to the first Journal Article Tag Suite Conference

The Journal Article Tag Suite has had a surprisingly quick acceptance since we released the first version in 2003. In this introduction I review how we got to where we are today, revisit some old controversies, define some terms, explain where "JATS" came from, and at least ask the question, "Is there anything left to do?"

## Conference Links

JATS-Con Home (http://jats.nlm.nih.gov/jats-con/)

Presentation Slides, Powerpoint (http://jats.nlm.nih.gov/jats-con/program/2010/presentations/beck.pptx)

Video of Presentation (http://videocast.nih.gov/summary.asp?Live=9728&start=361)