# Warfarin Therapy and VKORC1 and CYP Genotype

## Introduction

Warfarin (brand name Coumadin) is an anticoagulant (blood thinner). Warfarin acts by inhibiting the synthesis of vitamin K-dependent clotting factors II, VII, IX and X, and is used in the prevention and treatment of various thrombotic disorders (1). Warfarin is a drug with narrow therapeutic index; thus, a small change in its plasma levels can result in concentration-dependent adverse drug reactions or therapeutic failure. As such, the therapeutic dose of warfarin must be tailored for each individual based on response, which is measured by the INR (International Normalized Ratio), and the condition being treated (1).

There is a wide inter-individual variability —up to twenty-fold—in the dose of warfarin required to achieve therapeutic anticoagulation, and the time it takes to reach target INR. Approximately half of this variability is caused by both clinical or lifestyle factors (for example, an individual’s age, body mass index, gender, diet, smoking status, ethnicity/race, existing conditions, and concomitant medications) and by genetic variants in the VKORC1, CYP2C9 and CYP4F2 genes, and the CYP2C gene cluster rs12777823 variant (1).

The VKORC1 and CYP2C9 variants are the most important known genetic determinants of warfarin dosing. Warfarin targets VKORC1, an enzyme involved in vitamin K recycling. A common VKORC1 variant, c.-1639G>A, is associated with warfarin sensitivity and lower dose requirements. The CYP2C9 enzyme metabolizes S-warfarin, the more potent stereoisomer, and CYP2C9 variants with reduced activity are also associated with lower dose requirements (2).

The FDA-approved drug label for warfarin states that CYP2C9 and VKORC1 genotype information, when available, can assist in the selection of the initial and maintenance dose of warfarin. The label provides 2 sets of warfarin dosing recommendations, for when the CYP2C9 and VKORC1 genotypes are either known (Table 1) or not known (taking into account clinical factors, the initial dose of warfarin is usually 2–5 mg once daily and maintenance doses are typically 2–10 mg daily) (1).

The 2017 Update of the Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for Pharmacogenetics-Guided Warfarin Dosing provides warfarin dosing recommendations for adults and pediatric individuals. Recommendations from CPIC state that these dosing guidelines are applied after a warfarin dose has been calculated using a validated pharmacogenetic algorithm, which includes genotype information for VKORC1, c.-1639G>A and CYP2C9 (Figure 1) (2).

More recently, the Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Association for the Advancement of Pharmacy (KNMP (https://www.knmp.nl/)) has published recommendations for the initial standard dose of warfarin (3). A dose reduction is recommended for individuals who are CYP2C9 poor (PM) and intermediate metabolizers (IM) (with the exception of IM with the CYP2C9*1/*2 genotype, no dose change is required), and a dose reduction is recommended for individuals who have 2 copies of the VKORC1 c.-1639G>A variant allele (c.-1639G>A/A) (Table 2) (4, 5).

In addition, genetic variation in the CYP4F2 gene and a variant near the CYP2C gene cluster, rs12777823, have been associated with warfarin dosing. The CYP4F2*3 variant is associated with a modest increase in warfarin dose requirements, notably in individuals with European or Asian ancestry who are more likely to have this variant allele than other ancestral populations. Individuals with African ancestry are more likely than other ancestral groups to have the rs12777823 A/G or A/A genotype that has been associated with decreased warfarin dose requirements.

Table 1.

The FDA (2025) Drug Label for Warfarin. Ranges of Expected Maintenance Warfarin Doses based on CYP2C9 and VKORC1 Genotype.

VKORC1 | CYP2C9
VKORC1 | *1/*1 | *1/*2 | *1/*3 | *2/*2 | *2/*3 | *3/*3
GG | 5–7 mg | 5–7 mg | 3–4 mg | 3–4 mg | 3–4 mg | 0.5–2 mg
AG | 5–7mg | 3–4 mg | 3–4 mg | 3–4 mg | 0.5–2 mg | 0.5–2 mg
AA | 3–4 mg | 3–4 mg | 0.5–2 mg | 0.5–2 mg | 0.5–2 mg | 0.5–2 mg

Ranges are derived from multiple published clinical studies. The VKORC1, c.–1639G>A (rs9923231) variant is used in this table. Other co-inherited VKORC1 variants may also be important determinants of warfarin dose. Individuals with CYP2C9 *1/*3, *2/*2, *2/*3, and *3/*3 may require more prolonged time (>2–4 weeks) to achieve a maximum international normalized ratio (INR) effect for a given dosage regimen than individuals without these CYP variants. This table is adapted from the FDA-approved drug label for warfarin (1).

Table 2.

The DPWG Recommendations for Warfarin and CYP2C9 and VKORC1 Genotype (2025)

Phenotype/diplotype | Recommendation
CYP2C9*1/*2 | No action is required for this gene-drug interaction.
CYP2C9*1/*3 | Use 65% of the normal initial dose
CYP2C9*2/*2 | Use 65% of the normal initial dose
CYP2C9 IM (Other) | Use 65% of the normal initial dose
CYP2C9*2/*3^a^ | Use 45% of the normal initial dose
CYP2C9*3/*3^a^ | Use 20% of the normal initial dose
CYP2C9 PM (Other) | Use 20% of the normal initial dose
VKORC1 -1639GA^b^ | No action is required for this gene-drug interaction
VKORC1 -1639AA^b^ | Use 60% of the standard initial dose
VKORC1 -1639AA and CYP2C9 IM or PM | Both recommendations should be applied. Example: CYP2C9 IM (Other) and VKORC1 AA – Calculated as 60% of 65% of the normal dose: Use 40% of normal dose

CYP2C9 IM (Other): intermediate metabolizer, other genotype (decreased activity due to a variant with decreased activity other than *2 or *3)

CYP2C9 PM (Other): poor metabolizer, other genotype (strongly decreased activity due to the presence of 2 gene variants with decreased activity, at least one of which is other than *2 or *3)

^a^ As INR measurements are typically based on steady-state concentrations when warfarin is used, the observed influence of genotype on pharmacokinetics means that a longer time to reach this steady-state concentration must be taken into account. It may therefore be appropriate to monitor the INR later or for a longer period than usual at a stable dose.

^b^ The full names of the diplotypes are VKORC1 -1639GA (1173CT) and VKORC1 -1639AA (1173TT). The gene variants at the sites c.-1639 and c.1173 are in strong linkage disequilibrium (in other words, very strongly coupled). Therefore, the diplotype can be determined by genotyping at either site..

Table is adapted from (3, 4, 5) and (6).

## Drug: Warfarin

Warfarin is an anticoagulant used in the prevention and treatment of venous thrombosis, pulmonary embolism, and the complications associated with atrial fibrillation, or cardiac valve replacement, among other thromboembolic conditions(1). It can also be indicated to reduce the risk of stroke after a myocardial infarction (MI). Warfarin has no direct effect on an established thrombus (1). However, once a thrombus has occurred (for example, deep venous thrombosis), the goal of warfarin therapy is to prevent further extension of the formed clot and to prevent secondary thromboembolic complications that may be fatal (such as pulmonary embolism). Although the direct acting oral anticoagulants have largely superseded warfarin as first-line therapy in many clinical scenarios, warfarin is still prescribed in certain settings due to resource limitations and clinical indications (7, 8).

The FDA-approved drug label for warfarin has a boxed warning cautioning of the risk of bleeding, which can be fatal (1). Bleeding is more likely to occur within the first month, and risk factors include a high intensity of anticoagulation (INR greater than 4), age greater than or equal to 65, and a history of highly variable INRs. Other serious adverse events associated with warfarin therapy and proteins C and S levels include necrosis of the skin and other tissues, particularly when used prematurely to manage thrombosis associated with heparin-induced thrombocytopenia (HIT)(1, 9).

Warfarin exerts its anticoagulant effect by inhibiting the enzyme encoded by VKORC1, which catalyzes the conversion of vitamin K epoxide to the active reduced form of vitamin K, vitamin K hydroquinone. Vitamin K hydroquinone is an essential cofactor in the synthesis of several clotting factors and decreased availability of vitamin K hydroquinone leads to decreased activity of the clotting factors II, VII, IX, and X, and the anticoagulant proteins C and S (10).

Warfarin is orally administered as a racemic mixture of the R- and S- stereoisomers. The (S)-warfarin isomer is 2–5 times more potent than (R)-warfarin and primarily metabolized by CYP2C9, whereas (R)-warfarin is mainly metabolized by other cytochrome P450 enzymes (11).

Warfarin treatment requires monitoring of the international normalized ratio (INR) to facilitate appropriate and safe dosing based on intended use. The INR is a standardized measurement of prothrombin time prolongation, which is the time it takes for blood to clot. In healthy individuals, the INR is approximately one (range: 0.8–1.1). The goal of warfarin therapy is to achieve an INR in a target range for the condition being treated (most commonly 2–3).

Since warfarin is a drug with a narrow therapeutic index, an optimal starting dose may reduce the time taken to reach a stable INR and reduce the risk of having either a high INR (with a risk of bleeding) or a low INR (with a risk of thrombosis). Known factors that influence an individual’s response to the initial and maintenance doses of warfarin include clinical and lifestyle factors (for example, age, ethnicity/race, body weight, height, gender, concomitant medications—including those that inhibit the metabolism of warfarin, comorbidities, diet and nutritional status) and genetic factors (including CYP2C9 and VKORC1 genotype)(1, 12). As such, warfarin dosing can be modified to consider these and any additional personalized factors that may influence warfarin dose requirements. (1)

Warfarin is a teratogen – an agent that can cause abnormalities in a developing fetus. Therefore, warfarin use in pregnancy is contraindicated, except in women with mechanical heart valves who have a particularly high risk of thromboembolism. If warfarin is used in pregnancy, or if an individual becomes pregnant while taking warfarin, she should be informed of the potential risks to the fetus (1). Warfarin exposure in pregnancy can cause fetal death, neonatal death, or warfarin syndrome - a pattern of developmental abnormalities that most commonly affect bone and cartilage, causing nasal hypoplasia, and a “stippled” appearance to the ends of long bones. The risk of warfarin teratogenicity appears to be greatest between the 6^th^ and 12^th^ week of pregnancy, but toxicity before or after this period is still possible (13, 14). There is also an increased risk of bleeding at the time of delivery.

Warfarin is permitted during breastfeeding, as only small amounts pass into breastmilk and there have been no documented adverse effects in infants (15, 16). Clinical dosing of warfarin sometimes utilizes an initial loading dose to more rapidly reach the desired therapeutic dose needed. Huang and colleagues reported genotype-guided maintenance dosing with a genotype-scaled loading dose was useful to reduce the time to INR in the management of pulmonary embolism in postpartum women (15). The FDA-approved drug label recommends against the routine use of loading doses because this practice may increase hemorrhagic and other complications and does not offer more rapid protection against clot formation (1). However, loading doses are used in practice, and are addressed in CPIC recommendations (2).

The FDA-approved drug label for warfarin suggests considering a lower initial and maintenance dose of warfarin for elderly individuals, and in Asian ancestry individuals (1). There are insufficient, well-controlled studies regarding warfarin administration in any pediatric population, according to the FDA approved label (1). When used in children, dosing is based on adult data and recommendations. Pediatric individuals administered warfarin should avoid any activity or sport that may result in traumatic injury (1). If warranted in a pediatric individual, warfarin dosing and management should take into consideration the developmental changes affecting thrombosis and response to anticoagulants, with infants generally having much higher dose requirements as compared with adolescents to reach the desired INR (1).

The drug label also provides a dosing table of expected maintenance daily doses of warfarin based on CYP2C9 and VKORC1 genotype (Table 1). The label states that if the individual’s CYP2C9, VKORC1 or both genotypes are known, to consider these doses when selecting the initial dose of warfarin. However, multifactorial pharmacogenetic-based algorithms, such as the International Warfarin Pharmacogenetics Consortium (IWPC), have been shown to predict warfarin dose more precisely than the drug label table recommendations (2).

CPIC has provided warfarin dosing recommendations based on genetic factors that also incorporate certain variants more common among individuals of African ancestry (for example, CYP2C9*5, *6, *8, and *11, and rs12777823 (2). (Figure 1)

## Gene: VKORC1

The VKORC1 gene (located on chromosome 16p11.2) encodes the vitamin K epoxide reductase enzyme, which catalyzes the rate-limiting step in vitamin K recycling (by converting vitamin K epoxide to its reduced vitamin K form). This enzyme is also the target for warfarin.

A common promoter variant, VKORC1 c.-1639G>A (rs9923231), is associated with increased sensitivity to warfarin and lower dose requirements (17). Loss of function in the VKORC1 enzyme may impact hemostasis even in the absence of warfarin therapy. Variation at the VKORC1 locus has been associated with vascular dementia, ischemic stroke, and upper gastrointestinal bleeding (18, 19, 20). Variation in VKORC1 has also been hypothesized to associate with increased risk for osteopenia and osteoporosis, based on the role of vitamin K in bone physiology (21, 22). Perturbations in vitamin K homeostasis due to VKORC1 variation (rs9934438 C>T) have additionally been associated with increased risk of nephrolithiasis in sarcoidosis (23).

The rs9923231 variant in the promoter region of VKORC1 (NM_024006.4:c.-1639G>A) is associated with lower protein expression, and its frequency varies among different ethnic groups. The variant nucleotide of the polymorphism is the major allele (around 90%) in Asian populations and may be one of the contributing factors for lower warfarin dosing requirements often observed in individuals of Asian descent. It is also common in individuals of European descent (around 40%) and African Americans (around 14%) (24, 25, 26). The combined frequency of the AA and GA genotypes in a Peruvian cohort was reported to be 51.4% of 70 individuals on anticoagulant therapy (27). The minor allele frequency in a Sri Lankan population has been reported at approximately 10% (28). In genetically heterogeneous populations, such as Puerto Rico, the distribution of the VKORC1 c.-1639 A haplotype varies across subgroups in accordance with their relative ancestral contributions (29).

## The Cytochrome P450 Superfamily

The cytochrome P450 superfamily (CYP450) is a large and diverse group of enzymes that form the major system for metabolizing or detoxifying lipids, hormones, toxins, and drugs in the liver (30). The CYP450 genes are very polymorphic and can result in reduced, absent, or increased enzyme activity.

CYP450 isozymes involved in the metabolism of warfarin include CYP2C9, CYP3A4, and CYP1A2. The more potent warfarin S-enantiomer is metabolized by CYP2C9 while the R-enantiomer is metabolized by CYP1A2 and CYP3A4. The FDA-approved drug label for warfarin states that drugs that inhibit or induce CYP2C9, CYP1A2, CYP3A4 or any combination of these enzymes can influence warfarin exposure and increase or decrease the INR.

The influence of genetic variants in CYP2C9, CYP4F2, and the CYP2C gene cluster, is discussed below.

## Gene: CYP2C9

The CYP2C9 enzyme metabolizes approximately 15–20% of clinically used drugs, and atypical metabolic activity caused by genetic variants in the CYP2C9 gene can play a significant role in adverse drug reactions (31, 32). Among CYP2C isoforms expressed in the liver, CYP2C9 is the most abundant (33, 34).

The CYP2C9 gene (located on chromosome 10q23.22) is highly polymorphic, with more than 80 known alleles (35). The wild-type allele is designated CYP2C9*1. In a test of multiple CYP2C9 variants, when none of the tested variants are detected, the genotype is assigned as CYP2C9*1, and the gene is predicted to produce a fully functional enzyme with normal enzyme activity (36). Individuals who have 2 normal-function alleles, for example, CYP2C9*1/*1, are classified as “normal metabolizers” (Table 3).

Each allele is assigned an activity score of 0 (no-function), 0.5 (reduced-function), or 1 (normal-function), and the combined score for both alleles is used to determine the genetically inferred phenotype (metabolic status). The allele score system was initially used for CYP2D6 alleles and predicted phenotypes; however, it is now implemented by the Clinical Pharmacogenetics Implementation Consortium (CPIC) for a subset of other pharmacogenetic genes (33, 37).

A CYP2C9 diplotype with an activity score of 1.5 or 1 is classified as an IM phenotype, and diplotype activity scores of 0 or 0.5 are classified as PM (Table 3) (36). However, the effect of the reduced-function allele yielding a higher activity score than the no-function allele may result in different recommendations for IMs with activity scores of 1.5 and 1. For example, the CPIC guideline for the CYP2C9-phenytoin interaction recommends no adjustments are needed from typical dosing strategies for IMs with an activity score of 1.5, but recommends subsequent doses are reduced by 25% for IMs with an activity score of 1 (36).

Allelic variants associated with reduced or no enzyme activity include CYP2C9*2 (p.Arg144Cys), CYP2C9*3 (p.Ile359Leu), CYP2C9*5 (p.Asp360Glu), CYP2C9*8 (p.Arg150His), and CYP2C9*11 (p.Arg335Trp). The CYP2C9*2 reduced-function allele is more common in European (13%), Near Eastern (13%), and Central/South Asian (11%) populations than in Latino (8%), Oceanian (3%), East Asian (0.2%), or African (1–2%) descent populations (38). The CYP2C9*3 no-function allele is less common (<10% in most populations, except for Central/South Asian, at approximately 11%), and it is extremely rare in African populations. Notably, CYP2C9*3 has a reported minor allele frequency of 10.4% in a Sri Lankan population (28). In African descent populations, the CYP2C9*5 no-function (~1%), and CYP2C9*8 (6–8%), and CYP2C9*11 (1–3%) reduced-function alleles are also common. (39, 40, 41, 42).

Table 3.

The CPIC Assignment of likely CYP2C9 Phenotype based on Genotype

CYP2C9 phenotype^a,b^ | Genotype | Activity score | Examples of diplotype
Normal metabolizer | An individual with 2 normal-function alleles | 2 | *1/*1, *1/*9
Intermediate metabolizer | An individual with one normal-function allele plus one decreased-function allele OR one normal-function allele plus one no-function allele OR 2 decreased-function alleles | 1.5 | *1/*2, *1/*8
Intermediate metabolizer | An individual with one normal-function allele plus one decreased-function allele OR one normal-function allele plus one no-function allele OR 2 decreased-function alleles | 1 | *1/*3, *2/*2, *8/*11
Poor metabolizer | An individual with one no-function allele plus one decreased-function allele; OR 2 no-function alleles | 0.5 | *2/*3, *2/*6
Poor metabolizer | An individual with one no-function allele plus one decreased-function allele; OR 2 no-function alleles | 0 | *3/*3, *3/*6, *3/*5

^a^ Assignment of allele function and associated citations can be found at the CPIC website (https://cpicpgx.org/guidelines/cpic-guideline-for-nsaids-based-on-cyp2c9-genotype/), also see (43)

^b^ See the CYP2C9 Frequency Table (38) for population-specific allele and phenotype frequencies.

Note: There are no known cases of CYP2C9 ultrarapid metabolizers. CPIC - Clinical Pharmacogenetics Implementation Consortium

This table has been adapted from (42)

It should be noted that the definition of CYP2C9 IM and PM differs between the CPIC and the DPWG. Of specific interest is the DPWG determination that the increased risk of bleeding is small for individuals with CYP2C9*1/*2 genotype, and thus may be treated as NM with normal warfarin dosing and monitoring (4). The DPWG defines CYP2C9 IM as individuals with one normal-function allele and one decreased or no-function allele (except *2) and PM as individuals with 2 decreased or no-function alleles. Therefore, the DPWG defines IM OTHERWISE as individuals with one normal function allele and one decreased or no-function allele other than *2 and *3, for example *1/*5 or *1/*8. In addition, the DPWG defines PM OTHERWISE as individuals with 2 decreased or no-function alleles of which at least one other than *2 and *3, such as *3/*8 or *3/*11. (4)

## Gene: CYP4F2

Encoded by the CYP4F2 gene (located on chromosome 19p13.12), the CYP4F2 enzyme is involved in the hepatic metabolism of vitamin K. It is a vitamin K oxidase enzyme and is an important counterpart to VKORC1, a vitamin K reductase enzyme. While VKORC1 catalyzes vitamin K recycling, CYP4F2 limits the excessive accumulation of vitamin K in the liver by catalyzing the production of hydroxylated vitamin K, which is removed from the vitamin K cycle (44, 45). The CYP4F2 enzyme is also known to contribute to the metabolism of imatinib, fingolimod, and endogenous compounds including vitamin E, eicosanoids, leukotrienes, cholesterol, steroids, and other lipids (45).

The genetic variant CYP4F2*3 (NM_001082.5:c.1297C>T, rs2108622) has been shown to result in decreased CYP4F2 activity (45). The frequency of the variant T allele is approximately 30% in Europeans and Asians, and approximately 7% in African Americans (46) and over 45% in a Sri Lankan population (28). This variant is also part of the CYP4F2*4 haplotype along with rs3093105 (NM_001082.5:c.34T>G). Evidence suggests both CYP4F2*3 and *4 lead to reduced protein levels relative to the wild-type allele (CYP4F2*1) (45, 47). Analysis of the CYP4F2*11 allele (rs114396708, NM_001082.5:c.322C>T) in vitro suggests this variation destabilizes the holoenzyme to undetectable levels (47). It should be noted that clinical function status of CYP4F2 alleles are not established by CPIC at the time of publication (48).

Variation at the CYP4F2 locus can affect metabolism of its substrate medications but may also play a role in cardiovascular disease and hypertension risk (49). An association between the variant allele at rs2108622 (c.1297G>A) and hypertension and ischemic stroke in men has been reported (45).

Reduced function of CYP4F2 can also impact the metabolism of vitamin E (though hydroxylation reactions) and thus impact the dosing of vitamin E supplements in various conditions such as neurological disorders or nonalcoholic fatty liver disease (45). Variants c.34T>G (rs3093105) and c.1297G>A (rs2108622) may impact vitamin E hydroxylation, though the literature reports are unclear regarding the effects of these variants (45, 50).

## Gene: CYP2C Locus (rs12777823)

The rs12777823 variant, located in the CYP2C gene cluster on chromosome 10, is an inter-genic variant that also has been associated with reduced warfarin dose requirements but with much lower effect. The rs12777823 variant was associated with altered warfarin clearance, and individuals with this variant require a lower maintenance dose of warfarin than individuals who do not have this variant (51). A local-ancestry informed genome-wide association study in 2 African-American cohorts found another variant in the CYP2 locus, rs7906871 A>T, showed significant association with altered warfarin dosing requirements and correlated with alternative splicing at the CYP2C19 locus (52).

The rs12777823 variant is common in African Americans (allele frequency 25%) and is also common in other populations; for example, Japanese (32%), and European (15%). However, the association with warfarin dose requirement has only been found for African Americans (2, 53).

## Linking VKORC1, CYP2C9, CYP4F2, and CYP2C locus Genetic Variation with Treatment Response

It should be noted that the frequency of genetic variation at the VKORC1, CYP2C9, CYP4F2, and CYP2C loci can vary between specific ancestral groups with similar geographic origin. This has been reported for individuals of Hmong ancestry relative to other East Asian ancestral groups. The collective genotype data from approximately 400 individuals suggests that the rate of warfarin-sensitive individuals (those requiring a lower dose to achieve target INR) is 28% among Hmong population but only 5% in a more general East Asian cohort of over 1000 individuals (54). Additionally, region-specific subpopulations may benefit from different prescribing algorithms trained on a local population as compared with global guidelines. One study reported a comparative analysis of multiple national and regional pharmacogenomic dosing algorithms and found that locally derived models performed more accurately than CPIC or Gage dosing recommendations (55). Implementation of pharmacogenetic guided dosing should be paired with standard practice INR monitoring to account for additional physiological, environmental, or unknown genetic factors that influence safe warfarin dosing.

Multiple randomized controlled trials have been conducted to study warfarin dosing based on standard practice to genotype-guided dosing using either CYP2C9, VKORC1, or both (56, 57, 58, 59, 60, 61, 62, 63, 64, 65). While some studies were underpowered to detect differences (59), most found that genotype-guided prescribing of warfarin had a positive impact on dosing accuracy, time in the desired INR, or time to reach INR or stable dosing (57, 58, 60, 61, 62, 63, 64, 65). Some studies reported no differences in the treatment groups or subsets of their cohorts (66, 67) though the alleles tested in these early trials were limited to CYP2C*2, *3 and VKORC1. Meta-analyses of earlier trials were inconclusive (68, 69, 70) but as additional studies have been conducted, analyses support the importance of genotype-guided prescribing (71, 72, 73). Other studies have investigated inclusion of the CYP4F2 variant, but with uncertain results, possibly due to small number of CYP2C9 alleles also tested (74, 75).

VKORC1

Genetic variation in the VKORC1 gene is the most important known genetic factor that influences warfarin dosing. Pharmacogenomic algorithms for warfarin dosing routinely include testing for VKORC1 c.-1639G>A (rs9923231). Individuals starting warfarin therapy who have at least one “A” allele at rs9923231 require lower initial and maintenance doses compared with individuals with a G/G genotype at this locus. This has been reported in studies of multiple geographic and ancestral groups, though the frequency of the variant allele may differ between populations (17, 25, 28, 76, 77, 78, 79).

Less commonly, rare missense variants in VKORC1 can lead to warfarin resistance and higher dose requirements (80, 81).

CYP2C9

Compared with CYP2C9 normal metabolizers, individuals who have one or 2 copies of CYP2C9*2 or CYP2C9*3 are more sensitive to warfarin—they require lower doses and are at a greater risk of bleeding during warfarin initiation (82, 83, 84, 85, 86). Similar results have been reported in a Brazilian cohort as well as a Saudi cohort, with CYP2C9*2 or CYP2C9*3 positive individuals having lower maintenance warfarin doses compared with individuals without those alleles (76, 78).

Ndadza and colleagues reported on the factors with the strongest influence on warfarin dosing in a study of 503 individuals of southern African and mixed ancestry. Variation at rs12777823(G>A), CYP2C9*8, CYP2C9*11, and CYP2C8*2 were significantly associated with warfarin dose in black African participants. However, the mixed ancestry study participants had significant association with warfarin dosing and CYP2C9*2, CYP2C8*4, and VKORC1 c.-1639G>A. (53)

In African Americans, the CYP2C9*5, *6, *8, and *11 variant alleles are more prevalent and contribute to the variability in individual response to warfarin (87). These alleles are found more commonly in individuals with African ancestry, and collectively, are more common than the CYP2C9*2 and *3 alleles (2, 53, 79, 88, 89).

Evidence is emerging in other populations to support altered warfarin dosing based on CYP2C9 alleles less commonly seen in European ancestral backgrounds. One study of a Han Chinese atrial fibrillation cohort reported that CYP2C9*12, *16, and *60 were associated with lower stable doses (90). Additional studies suggest that among Hispanic populations, alleles such as CYP2C9*5, *8, *11, and *61 and other CYP2C9 variants (rs202201137) may also play a notable role in warfarin dose requirements (91, 92, 93, 94). Rare variants found in a large Japanese cohort studied in vitro also displayed reduced CYP2C9 activity (relative to CYP2C9*1) toward S-warfarin (95). These reports underscore the need to expand functional and clinical analyses of pharmacogenetic variants in multiple populations to better inform pharmacogenetic implementation.

CYP4F2

The CYP4F2*3 allele has been associated with decreased enzyme function and higher doses of warfarin to achieve therapeutic anticoagulation (by inhibiting vitamin K-dependent clotting factors) (44). The first studies of CYP4F2 and warfarin dosing reported that European ancestry individuals with the variant rs2108622 TT genotype required approximately 1 mg/day more warfarin than individuals with the rs2108622 CC genotype (46). Two meta-analyses concluded that “T carriers” (individuals with CT or TT genotypes) require approximately an 8–11% increase in warfarin dose, compared with CC individuals. However, data did not support CYP4F2 influencing warfarin requirements in African Americans (96, 97).

The inclusion of this CYP4F2 variant in warfarin dosing models moderately improves the accuracy of warfarin dose prediction for individuals of European or Asian ancestry, but not for individuals of African ancestry. Accordingly, CPIC recommends that the dose of warfarin should be increased by 5–10% in non-African American individuals who have the CYP4F2*3 variant (optional recommendation). CPIC makes no recommendation for African Americans, stating that data do not support an impact of this variant on warfarin dosing in those of African ancestry (moderate recommendation) (2, 96, 97). Additional studies in a Saudi population reported variation at the CYP4F2 locus did not associate with differences in dose requirements for these individuals (78).

CYP2C Locus

The association with warfarin dose requirement and variation at rs12777823 has only been found for individuals of African descent (52, 53, 98). Individuals who are heterozygous for the rs12777823 A allele require a dose reduction of warfarin by 7 mg/week, and individuals who are homozygous for the rs12777823 A allele require a dose reduction of warfarin by 9 mg/week (51). Data are lacking for the role of rs12777823 and warfarin response in other populations.

Some pharmacogenomic dosing algorithms do not include rs12777823 status, but analysis has shown that the addition of this variant improves the dosing algorithm published by the IWPC by 21% for African Americans (51).

CPIC has stated that for African Americans, a dose reduction of 10–25% in individuals with the rs12777823 A/G or A/A genotypes are recommended (moderate recommendation). For non-African Americans, CPIC recommends that rs12777823 should not be considered, even if the result is available (2).

## Genetic Testing

The NIH’s Genetic Testing Registry (GTR®) provides a list of tests for warfarin response (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?scope=tests&term=C0750384&fs=C0750384), and the VKORC1 (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=79001%5bgeneid%5d), CYP2C9 (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1559%5bgeneid%5d), and CYP4F2 (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=8529%5bgeneid%5d) genes as well as the rs12777823 (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?scope=tests&term=rs12777823&fs=rs12777823) variant.

The VKORC1 and CYP2C9 genotypes are important genetic determinants of warfarin dosing. The contribution of VKORC1 to the variation in dose requirement is larger (approximately 30%) than the contribution of CYP2C9 (usually less than 10%) (99). The variants that are used in the FDA table to guide therapy are CYP2C9*2, CYP2C9*3, and VKORC1, c.−1639G>A.

The Association for Molecular Pathology (AMP) has published recommendations for clinical warfarin genotyping allele selection (12). The Tier 1 alleles (recommended for all tests due to known clinical impact, frequency, and readily available reference materials) include CYP2C9*2, CYP2C9*3, CYP2C9*5, CYP2C9*6, CYP2C9*8, CYP2C9*11, and VKORC1 c.-1639G>A. (Table 4)

The AMP Tier 2 alleles (known or strongly suspected clinical impact, reference materials may or may not be available) are CYP2C9*12, *13, *15, CYP2F4*3, VKORC1 rs72547529 and rs61742245, as well as rs12777823 in the CYP2C gene cluster. (Table 5)

Table 4:

Tier 1 Alleles for genetic testing, AMP (2020)

Gene | Allele | Functional status | Defining functional variant | Multiethnic allele frequency (range), %
CYP2C9 | *2 | Decreased function | rs1799853 | 0–12
CYP2C9 | *3 | Decreased function | rs1057910 | 1–11
CYP2C9 | *5 | Decreased function^a^ | rs28371686 | 0–1
CYP2C9 | *6 | No function | rs9332131 | 0–1
CYP2C9 | *8 | Decreased function^a^ | rs7900194 | 0–5
CYP2C9 | *11 | Decreased function^a^ | rs28371685 | 0–2
VKORC1 | c.-1639G>A | Decreased expression | rs9923231 | 10–88

Table adapted from (12)

^a^ Functional status from PharmVar (accessed Feb 2026).

Table 5:

Tier 2 Alleles for genetic testing, AMP (2020)

Gene | Allele | Functional status | Defining functional variant | Multiethnic allele frequency (range), %
CYP2C9 | *12 | Decreased function^a^ | rs9332239 | 0–0.3
CYP2C9 | *13 | No function^a^ | rs72558187 | 0–0.2
CYP2C9 | *15 | No function | rs72558190 | 0–0.01
CYP4F2 | *3 | Possibly decreased function | rs2108622 | 10–40
VKORC1 | None | Warfarin resistant | rs72547529 | 0–0.25
VKORC1 | None | Warfarin resistant | rs61742245 | 0–3.8
2C Cluster | None | Unknown^b^ | rs12777823 | 0–30

Table adapted from (12)

^a^ Functional status from PharmVar (accessed Feb 2026).^b^Variant is in linkage disequilibrium with warfarin effect in individuals of West African ancestry.

In addition to molecular testing from accredited clinical laboratories, there are point-of-care tests for genotyping to support pharmacogenomic guided dosing. Systems and kits to test for CYP2C19, CYP2C9, VKORC1, and other variant loci have been developed and tested for feasibility in clinic (60, 100, 101, 102, 103, 104, 105, 106) . Point-of-care (POC) testing generally results in a more rapid turnaround of testing results to support quicker clinical decisions than traditional laboratory testing (107, 108). However, POC testing kits often test only a small number of genetic variants and thus may not include all the variants of interest (106).

Few tests in the NIH Genetic Testing Registry test for the presence of rs12777823 (5 versus more than 60 tests for warfarin response, as of 6 March 2026). Other variants that are not routinely tested for include the CYP2C9*5, *6, *8 and *11 alleles, the genes CYP4F2, EPHX1, NQO1 and GGCX (which all have a role in the vitamin K cycle), and the gene CALU (a cofactor in the VKOR complex) (87, 109, 110, 111, 112).

In African Americans, the influence of the CYP2C9*5, *6, *8 and *11 alleles are thought to be as significant as the influence of the CYP2C9*2 and*3 alleles on warfarin dosing in Europeans. Testing for these additional CYP2C9 alleles, and incorporating the resulting genotype into an expanded dosing algorithm improves warfarin dose prediction in African Americans and in other populations with substantial African ancestry (for example, Caribbean Hispanics and Brazilians), while maintaining high performance in European-Americans (113).

Individuals who are most likely to benefit from genetic testing are include those who have yet to start warfarin therapy, elderly individuals on multiple medications (polypharmacy), and those with contraindications to newer direct oral anticoagulants (DOACs) (for example, mechanical heart valve replacement, significant liver diseases, end-stage kidney disease, high-risk antiphospholipid syndrome). Some studies have reported that, in general, the current use of genotype-guided dosing algorithms did not improve anticoagulation control in the first few weeks of warfarin therapy (66, 68, 114, 115, 116, 117); however, another study found genotype-guided warfarin dosing did improve the safety of starting warfarin, compared with clinically guided dosing (60, 118). Other reports have found that genotype-informed warfarin dosing improved clinical outcomes (reduced hospitalizations, increased time in the desired INR) and improved the rate of achieving the target INR (63, 98, 119).

## The CYP2C9 and CYP4F2 Genes Interactions with Medications Used for Additional Indications

The CYP2C9 enzyme plays a role in the metabolism of multiple medications used for indications other than anticoagulation.

- Pain management: Non-steroid anti-inflammatory medications including celecoxib, flurbiprofen, lornoxicam, and ibuprofen are metabolized by CYP2C9. For individuals with intermediate or poor metabolism, dose reduction may be needed to reduce the risk of toxicities from high plasma levels of the medication.
- Antiepileptic medications: Phenytoin is metabolized by CYP2C9 and individuals with reduced activity may experience higher exposure and increased risk of side effects such as sedation, nystagmus, and ataxia.
- Multiple sclerosis: Siponimod, a sphingosine-1-phosphate receptor modulator, should not be used in CYP2C9 *3/*3 genotyped individuals, as this is a critical enzyme in drug metabolism and high drug levels can trigger bradycardia. Other reduced- or no-function CYP2C9 alleles may also warrant reduced dosing.
- Appetite stimulant: Individuals with AIDS-related anorexia or chemotherapy related nausea and vomiting may be prescribed dronabinol, which is metabolized by CYP2C9. CYP2C9 poor metabolizers are at risk of adverse effects including sedation, physical weakness and palpitations.
- Gout: Lesinurad, a urate transport inhibitor, is metabolized by CYP2C9 and poor metabolizers have an increased risk of side effects such as kidney stones or other kidney problems.

The CYP4F2 enzyme is reported to be involved in the metabolism of multiple medications, including tyrosine kinase inhibitor imatinib, immunomodulator fingolimod, and antibiotics such as linezolid (45).

Additional information can be found at ClinPGx (http://www.clinpgx.org), CPIC (https://www.clinpgx.org/cpic/pairs), and the FDA (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling) (search for “CYP2C9” or “CYP4F2”)

## Therapeutic Recommendations Based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

### 2025 Statement from the US Food and Drug Administration (FDA)

Initial and Maintenance Dosing

The appropriate initial dosing of warfarin sodium tablets varies widely for different patients. Not all factors responsible for warfarin dose variability are known, and the initial dose is influenced by:

- Clinical factors including age, race, body weight, sex, concomitant medications, and comorbidities
- Genetic factors (CYP2C9 and VKORC1 genotypes)

Select the initial dose based on the expected maintenance dose, taking into account the above factors. Modify this dose based on consideration of patient-specific clinical factors. Consider lower initial and maintenance doses for elderly and/or debilitated patients and in Asian patients. Routine use of loading doses is not recommended as this practice may increase hemorrhagic and other complications and does not offer more rapid protection against clot formation.

Individualize the duration of therapy for each patient. In general, anticoagulant therapy should be continued until the danger of thrombosis and embolism has passed.

Dosing Recommendations without Consideration of Genotype

If the patient’s CYP2C9 and VKORC1 genotypes are not known, the initial dose of warfarin sodium tablets is usually 2 to 5 mg once daily. Determine each patient’s dosing needs by close monitoring of the INR response and consideration of the indication being treated. Typical maintenance doses are 2 to 10 mg once daily.

Dosing Recommendations with Consideration of Genotype

Table 1 displays three ranges of expected maintenance warfarin sodium tablets doses observed in subgroups of patients having different combinations of CYP2C9 and VKORC1 gene variants. If the patient’s CYP2C9 and/or VKORC1 genotype are known, consider these ranges in choosing the initial dose. Patients with CYP2C9 *1/*3, *2/*2, *2/*3, and *3/*3 may require more prolonged time (>2 to 4 weeks) to achieve maximum INR effect for a given dosage regimen than patients without these CYP variants.

Please review the complete therapeutic recommendations that are located here: (1)

### 2025 Summary of recommendations from the Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Association for the Advancement of Pharmacy (KNMP)

VKORC1 -1639 GA: warfarin[e]

NO action is required for this gene-drug interaction.

The genetic variation results in a reduction in the required dose and an increase in the risk of excessively severe inhibition of blood clotting during the first month of the treatment. However, the effect is small and GA is also the most common genotype, meaning that the standard treatment will primarily be based on patients with this genotype.

VKORC1 -1639 AA: warfarin[e]

The genetic variation results in increased sensitivity to warfarin. This results in an increase in the risk of [excessive anticoagulation] (INR >4) during the first month of the treatment. [The genetic variation leads to increased sensitivity to warfarin.]

- use 60% of the standard initial dose

The calculation of the genotype-specific starting and maintenance doses can be performed using an algorithm, such as that used in EU-PACT. https://www.knmp.nl/dossiers/farmacogenetica

If an algorithm is not used and the patient also has a CYP2C9 genetic variation requiring a reduction in the starting dose: apply both dose recommendations. So if the CYP2C9 recommendation is to use 65% of the normal starting dose, use 60% of 65% (= 39%, rounded to 40%) of the normal starting dose.

CYP2C9*1/*2: warfarin

NO action is required for this gene-drug interaction.

Genetic variation may lead to a decrease in the required maintenance dose. However, there is insufficient evidence that this causes problems when therapy is initiated as usual.

CYP2C9*2/*2: warfarin and CYP2C9*1/*3: warfarin

The risk of bleeding is increased. The genetic variation reduces the conversion of warfarin into inactive metabolites.

- use 65% of the normal initial dose

The calculation of the genotype-specific starting and maintenance doses can be performed using an algorithm, such as that used in EU-PACT.

CYP2C9*2/*3: warfarin

The risk of bleeding may be increased. The genetic variation reduces the conversion of warfarin into inactive metabolites.

- use 45% of the normal initial dose

Note: As INR measurements are typically based on steady-state concentrations when warfarin is used, the observed influence of genotype on pharmacokinetics means that a longer time to reach this steady-state concentration must be taken into account. It may therefore be appropriate to monitor the INR later or for a longer period than usual at a stable dose.

The calculation of the genotype-specific starting and maintenance doses can be performed using an algorithm, such as that used in EU-PACT.

CYP2C9 IM OTHERWISE: warfarin

This gene variation reduces the conversion of warfarin to inactive metabolites. This can increase the risk of bleeding.

Recommendation:

- use 65% of the normal initial dose

The genotype-specific initial dose and maintenance dose can be calculated using an algorithm. Algorithms for Caucasian patients usually contain only the *2 and *3 allele. If the activity of the reduced-activity allele is comparable to the activity of *2 or *3, then the algorithm can be completed as if *1/*2 or \1/*3 is present. [ Separate dosing algorithms have been developed for patients of African or (East) Asian descent.]

CYP2C9 PM OTHERWISE: warfarin

The risk of bleeding may be increased. The genetic variation reduces the conversion of warfarin into inactive metabolites..

Recommendation:

- use 20% of the normal initial dose

The calculation of the genotype-specific starting and maintenance doses can be performed using an algorithm.

Algorithms for Caucasian patients usually only include the *2 and *3 alleles. If the activity of the reduced-activity allele is comparable to that of *2 or *3, the algorithm can be applied as if *2 or *3 were present.

Modified dose algorithms have been developed for patients of African or (East) Asian descent.

Please review the complete therapeutic recommendations located here: (3, 4, 5) Updates to published text from (6).

### 2017 Statement from the Clinical Pharmacogenetics Implementation Consortium (CPIC)

Non-African ancestry recommendation

In patients who self-identify as non-African ancestry, the recommendation is to:

1 Calculate warfarin dosing using a published pharmacogenetic algorithm, including genotype information for VKORC1-1639G>A and CYP2C9*2 and *3. In individuals with genotypes associated with CYP2C9 poor metabolism (e.g., CYP2C9 *2/*3, *3/*3) or both increased sensitivity (VKORC1-1639 A/A) and CYP2C9 poor metabolism, an alternative oral anticoagulant might be considered. The bulk of the literature informing these recommendations is in European and Asian ancestry populations, but consistent data exist for other non-African populations. These recommendations are graded as STRONG.
2 If a loading dose is to be utilized, the EU-PACT loading dose algorithm that incorporates genetic information could be used. This recommendation is OPTIONAL.
3 While CYP2C9*5, *6, *8, or *11 variant alleles are commonly referred to as African-specific alleles, they can occur among individuals who do not identify as, or know of their, African ancestry. If these variant alleles are detected, decrease calculated dose by 15–30% per variant allele or consider an alternative agent. Larger dose reductions might be needed in patients homozygous for variant alleles (i.e., 20–40%, e.g., CYP2C9*2/*5). This recommendation is graded as OPTIONAL.
4 If the CYP4F2*3 (i.e., c.1297A, p.433Met) allele is also detected, increase the dose by 5–10%. This recommendation is also considered OPTIONAL.
5 The data do not suggest an association between rs12777823 genotype and warfarin dose in non-African Americans, thus rs12777823 should not be considered in these individuals (even if available).

African ancestry recommendation

In patients of African ancestry, CYP2C9*5, *6, *8, *11 are important for warfarin dosing. If these genotypes are not available, warfarin should be dosed clinically without consideration for genotype. If CYP2C9*5, *6, *8, and *11 are known, then the recommendation is to:

1 Calculate warfarin dose using a validated pharmacogenetic algorithm, including genotype information for VKORC1 c.-1639G>A and CYP2C9*2 and *3;
2 If the individual carries a CYP2C9*5, *6, *8, or *11 variant allele(s), decrease calculated dose by 15–30%. Larger dose reductions might be needed in patients who carry two variant alleles (e.g., CYP2C9*5/*6) (i.e., 20–40% dose reduction).
3 In addition, rs12777823 is associated with warfarin dosing in African Americans (mainly originating from West Africa). Thus, in African Americans a dose reduction of 10–25% in those with rs12777823 A/G or A/A genotype is recommended. These recommendations are considered MODERATE.

In individuals with genotypes that predict CYP2C9 poor metabolism or who have increased warfarin sensitivity (VKORC1 c.-1639 A/A) and CYP2C9 poor metabolism, an alternative oral anticoagulant should be considered (see Supplemental Material for definitions of strength of recommendations). As noted above, for non-African ancestry, if a loading dose is to be used, the EU-PACT algorithm that incorporates genetic information could be used to calculate loading dose. This recommendation is OPTIONAL. The data do not support an impact on clinical phenotype for CYP4F2 on warfarin dosing in those of African ancestry and so no recommendation is made for use of CYP4F2 genotype data in blacks.

Please review the complete therapeutic recommendations, including recommendations for pediatric patients, located here: (2).

## Nomenclature for Selected Alleles

Nomenclature for selected CYP2C9 alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2C9*2 ^[1]^ | 430C>T Arg144Cys | NM_000771.4:c.430C>T (http://www.ncbi.nlm.nih.gov/clinvar/variation/8409/) | NP_000762.2:p.Arg144Cys | rs1799853 (https://www.ncbi.nlm.nih.gov/snp/rs1799853)
CYP2C9*3 ^[1]^ | 1075A>C Ile359Leu | NM_000771.4:c.1075A>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/8408/) | NP_000762.2:p.Ile359Leu | rs1057910 (https://www.ncbi.nlm.nih.gov/snp/rs1057910)
CYP2C9*5 ^[1]^ | 1080C>G Asp360Glu | NM_000771.4:c.1080C>G (https://www.ncbi.nlm.nih.gov/clinvar/variation/225984/) | NP_000762.2:p.Asp360Glu | rs28371686 (https://www.ncbi.nlm.nih.gov/snp/rs28371686)
CYP2C9*6 ^[1]^ | 817delA Lys273Argfs | NM_000771.4:c.817delA (https://www.ncbi.nlm.nih.gov/clinvar/variation/285601/) | NP_000762.2:p.Lys273Argfs | rs9332131 (https://www.ncbi.nlm.nih.gov/snp/rs9332131)
CYP2C9*8 ^[1]^ | 449G>A Arg150His | NM_000771.4:c.449G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/226024/) | NP_000762.2:p.Arg150His | rs7900194 (https://www.ncbi.nlm.nih.gov/snp/rs7900194)
CYP2C9*11 ^[1]^ | 1003C>T Arg335Trp | NM_000771.4:c.1003C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/370010/) | NP_000762.2:p.Arg335Trp | rs28371685 (https://www.ncbi.nlm.nih.gov/snp/rs28371685)
CYP2C9*12 ^[2]^ | 1465C>T Pro489Ser | NM_000771.4:c.1465C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/3253607/) | NP_000762.2:p.Pro489Ser | rs9332239 (https://www.ncbi.nlm.nih.gov/snp/rs9332239)
CYP2C9*13 ^[2]^ | 269T>C Leu90Pro | NM_000771.4:c.269T>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/3253602/) | NP_000762.2:p.Leu90Pro | rs72558187 (https://www.ncbi.nlm.nih.gov/snp/rs72558187)
CYP2C9*15 ^[2]^ | 485C>A Ser162X | NM_000771.4:c.485C>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/3253605/) | NP_000762.2:p.Ser162Ter | rs72558190 (https://www.ncbi.nlm.nih.gov/snp/rs72558190)

HGVS - Human Genome Variation Society, dbSNP - Single Nucleotide Polymorphism Database

^[1]^ AMP Tier 1 allele (12)

^[2]^ AMP Tier 2 allele (12)

Pharmacogenetic Allele Nomenclature: International Workgroup Recommendations for Test Result Reporting (120).

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (http://www.hgvs.org/content/guidelines)).

Nomenclature for Cytochrome P450 enzymes is available from Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium (121).

Nomenclature for selected VKORC1 alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
-1639G>A^[1]^ | 1173C>T | NM_024006.5:c.-1639G>A (http://www.ncbi.nlm.nih.gov/clinvar/variation/2211/) | Not applicable - variant occurs in a non-coding region | rs9923231 (https://www.ncbi.nlm.nih.gov/snp/rs9923231)
c.196G>A^[2]^ | p.Val66Met | NM_024006.6:c.196G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/692018/?term=((679794%5BAlleleID%5D))) | NP_076869.1:p.Val66Met | rs72547529 (https://www.ncbi.nlm.nih.gov/snp/rs72547529)
c.106G>T ^[2]^ | p.Asp36Tyr | NM_024006.6:c.106G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/2212/?term=((17251%5BAlleleID%5D))) | NP_076869.1:p.Asp36Tyr | rs61742245 (https://www.ncbi.nlm.nih.gov/snp/rs61742245)

HGVS - Human Genome Variation Society, dbSNP - Single Nucleotide Polymorphism Database

^[1]^ AMP Tier 1 allele (12)

^[2]^ AMP Tier 2 allele (12)

Pharmacogenetic Allele Nomenclature: International Workgroup Recommendations for Test Result Reporting (120).

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (http://www.hgvs.org/content/guidelines)).

Nomenclature for Cytochrome P450 enzymes is available from Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium (121).

Nomenclature for selected CYP4F2 alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP4F2*3 ^[2]^ | 1297G>A Val433Met | NM_001082.4:c.1297G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/225969/) | NP_001073.3:p.Val433Met | rs2108622 (https://www.ncbi.nlm.nih.gov/snp/rs2108622)

HGVS - Human Genome Variation Society, dbSNP - Single Nucleotide Polymorphism Database

^[2]^ AMP Tier 2 allele (12)

Pharmacogenetic Allele Nomenclature: International Workgroup Recommendations for Test Result Reporting (120).

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (http://www.hgvs.org/content/guidelines)).

Nomenclature for Cytochrome P450 enzymes is available from Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium (121).

Nomenclature for rs12777823

HGVS reference sequence | dbSNP reference identifier for allele location
NC_000010.11:g.94645745G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/225947/) (GRCh38) ^[2]^ NC_000010.10:g.96405502G>A (GRCh37) | rs12777823 (https://www.ncbi.nlm.nih.gov/projects/SNP/snp_ref.cgi?rs=12777823)

HGVS - Human Genome Variation Society, dbSNP - Single Nucleotide Polymorphism Database

^[2]^ AMP Tier 2 allele (12)

Pharmacogenetic Allele Nomenclature: International Workgroup Recommendations for Test Result Reporting (120).

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS (http://www.hgvs.org/content/guidelines)).

## Acknowledgments

Version 4.0 (June 16, 2026): The authors would like to thank Jorge Duconge Soler, PhD, MSc, BSc Pharm, Professor of Pharmacokinetics and Pharmacogenomics, Department of Pharmaceutical Sciences, University of Puerto Rico School of Pharmacy, Medical Sciences Campus, San Juan, Puerto Rico, USA, and Marga Nijenhuis, PhD, Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands for providing an expert review of this summary.

Version 3.0 (June 11, 2018):

The author would like to thank the following experts for reviewing this summary:Saeed Alzghari, MS, MBA (HOM), PharmD, BCPS, Director of Clinical Pharmacy, Gulfstream Genomics, Dallas, TX, USA; Bernard Esquivel, MD, PhD, MHA, President of the Latin American Association for Personalized Medicine, Mexico City, Mexico; Christine M. Formea, PharmD, BCPS, FCCP, FASHP, Pharmacogenomics Medication Therapy Management Pharmacist and Assistant Professor of Pharmacy, Mayo Clinic College of Medicine and Science, Rochester, MN, USA; Inge Holsappel, Pharmacist at the Royal Dutch Pharmacists Association (KNMP), the Hague, the Netherlands (for reviewing the information regarding the guidelines of the DPWG); George P. Patrinos, Associate Professor of Pharmacogenomics and Pharmaceutical Biotechnology, Department of Pharmacy, University of Patras, Patras, Greece; Chakradhara Rao S Uppugunduri, Maître-assistant at the CANSEARCH Laboratory, Department of Pediatrics, University of Geneva, Geneva, Switzerland.

Version 2.0 (2016):

The author would like to thank Brian F. Gage, MD, MSC, Professor of Medicine, Washington University, St. Louis, MO, USA; and Sol Schulman, MD, Clinical Fellow in Medicine, Division of Hemostasis and Thrombosis, Department of Medicine, Beth Israel Deaconess Medical Center, Harvard Medical School, Boston, MA, for reviewing this summary.

Version 1.0 (2012/2013):

The Pharmacogenomics Knowledgebase: http://www.pharmgkb.org

The Clinical Pharmacogenetics Implementation Consortium: http://www.pharmgkb.org/page/cpic

## Version History

To view the 2018 version of this summary (Created: June 11, 2018) please click here.

To view the 2016 version of this summary (Created: June 8, 2016) please click here.

To view the 2013 version of this summary (Created: March 18, 2013) please click here.

## References

1 Warfarin Sodium table. Parsippany, NJ, USA: Teva Pharmaceuticals USA Inc.; 2025. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=0cbce382-9c88-4f58-ae0f-532a841e8f95.
2 Johnson, J.A., K.E. Caudle, L. Gong, M. Whirl-Carrillo, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for Pharmacogenetics-Guided Warfarin Dosing: 2017 Update. Clin Pharmacol Ther, 2017. 102(3): p. 397–404.28198005
3 Pharmacogenetic Recommendation Text [Cited Feb. 12, 2026]. Available from https://www.knmp.nl/dossiers/farmacogenetica/pharmacogenetics.
4 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharmacogenetic Guidelines [Internet]. Netherlands. CYP2C9: warfarin [Cited Feb. 19, 2026]. Available from https://www.g-standaard.nl/risicoanalyse/M0005776.pdf.
5 Royal Dutch Pharmacists Association (KNMP). Dutch Pharmacogenetics Working Group (DPWG). Pharmacogenetic Guidelines [Internet]. Netherlands. VKORC1: Warfarin [Cited Feb. 19, 2026]. Available from https://www.g-standaard.nl/risicoanalyse/M0005779.pdf.
6 Nijenhuis, M., Personal communication. 2026.
7 Julia, S. and U. James, Direct Oral Anticoagulants: A Quick Guide. Eur Cardiol, 2017. 12(1): p. 40–45.30416551
8 Ingelman-Sundberg, M. and M. Pirmohamed, Precision medicine in cardiovascular therapeutics: Evaluating the role of pharmacogenetic analysis prior to drug treatment. J Intern Med, 2024. 295(5): p. 583–598.38343077
9 Mohamed Osman, R., A. Suliman, R. Mohamedosman, T. Tahameed, et al., Warfarin-induced skin necrosis: a narrative review of clinical features, risk factors, and treatment strategies. Ann Med Surg (Lond), 2025. 87(11): p. 7249–7260.41180656
10 ClinPGx [Internet]. Palo Alto (CA): Stanford University. Warfarin Pathway Pharmacodynamics: Simplified diagram of the target of warfarin action and downstream genes and effects [Cited 2012 Feb 24]. Available from https://www.clinpgx.org/pathway/PA145011114.
11 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Warfarin Pathway Pharmacokinetics: Representation of the candidate genes involved in transport, metabolism and clearance of warfarin [Cited 2012 Feb 24]. Available from https://www.clinpgx.org/pathway/PA145011113.
12 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, H. Hachad, et al., Recommendations for Clinical Warfarin Genotyping Allele Selection: A Report of the Association for Molecular Pathology and the College of American Pathologists. J Mol Diagn, 2020. 22(7): p. 847–859.32380173
13 Basu, S., P. Aggarwal, N. Kakani, and A. Kumar, Low-dose maternal warfarin intake resulting in fetal warfarin syndrome: In search for a safe anticoagulant regimen during pregnancy. Birth Defects Res A Clin Mol Teratol, 2016. 106(2): p. 142–7.26389802
14 UpToDate. Use of anticoagulants during pregnancy and postpartum [Cited October 10, 2017]. Available from https://www.uptodate.com/contents/use-of-anticoagulants-during-pregnancy-and-postpartum.
15 Huang, W., H. Sun, L. Zhou, Y. Chen, et al., Application of Loading Dose Warfarin in Postpartum Women with Pulmonary Embolism - a Prospective, Randomized, Double-Blind Trial. Drug Des Devel Ther, 2025. 19: p. 10437–10448.41321667
16 Warfarin, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/30000196.
17 ClinPGx [Internet]. Palo Alto (CA): Stanford University. VIP Variant in VKORC1 [Cited 2012 Feb 24]. Available from https://www.clinpgx.org/variant/PA166155091.
18 Mur, J., D.L. McCartney, D.I. Chasman, P.M. Visscher, et al., Variation in VKORC1 Is Associated with Vascular Dementia. J Alzheimers Dis, 2021. 80(3): p. 1329–1337.33682710
19 Ilut, S., S.C. Vesa, V. Vacaras, D. Sipos-Lascu, et al., Association among VKORC1 rs9923231, CYP4F2 rs2108622, GGCX rs11676382 polymorphisms and acute ischemic stroke. Medicine (Baltimore), 2023. 102(34): p. e34836.37653796
20 Forgerini, M., G. Urbano, T.R. De Nadai, S.S. Batah, et al., The role of CYP2C9*2, CYP2C9*3 and VKORC1-1639 variants on the susceptibility of upper gastrointestinal bleeding: A full case-control study. J Pharm Pharm Sci, 2023. 26: p. 11136.36942299
21 He, J., H. Xie, C. Yan, Y. Sun, et al., Genetic Variation in VKORC1 and Risk for Osteoporosis. Arch Med Res, 2021. 52(2): p. 211–216.33234259
22 Vesa, S.C., V.M. Ichim, S. Ilut, S. Miglietta, et al., Association Between VKORC1 Gene Polymorphisms and Osteopenia and Osteoporosis: A Systematic Review and Meta-Analysis. Medicina (Kaunas), 2026. 62(1).41597466
23 Drent, M., P. Wijnen, O. Bekers, and A. Bast, Is a Vitamin K Epoxide Reductase Complex Subunit 1 (VKORC1) Polymorphism a Risk Factor for Nephrolithiasis in Sarcoidosis? Int J Mol Sci, 2024. 25(8).38674033
24 Geisen, C., M. Watzka, K. Sittinger, M. Steffens, et al., VKORC1 haplotypes and their impact on the inter-individual and inter-ethnical variability of oral anticoagulation. Thrombosis and haemostasis, 2005. 94(4): p. 773–9.16270629
25 Obayashi, K., K. Nakamura, J. Kawana, H. Ogata, et al., VKORC1 gene variations are the major contributors of variation in warfarin dose in Japanese patients. Clinical pharmacology and therapeutics, 2006. 80(2): p. 169–78.16890578
26 Ross, K.A., A.W. Bigham, M. Edwards, A. Gozdzik, et al., Worldwide allele frequency distribution of four polymorphisms associated with warfarin dose requirements. Journal of human genetics, 2010. 55(9): p. 582–9.20555338
27 Oscanoa, T.J., M.L. Guevara-Fujita, R.M. Fujita, M.Y. Munoz-Paredes, et al., Association between polymorphisms of the VKORC1 and CYP2C9 genes and warfarin maintenance dose in Peruvian patients. Br J Clin Pharmacol, 2024. 90(3): p. 769–775.37940132
28 Ranasinghe, P., N. Sirisena, V. Senadeera, G. Anandagoda, et al., Diversity of pharmacogenomic variants affecting warfarin metabolism in Sri Lankans. Pharmacogenomics, 2022. 23(17): p. 917–923.36285665
29 Villagra, D., J. Duconge, A. Windemuth, C.L. Cadilla, et al., CYP2C9 and VKORC1 genotypes in Puerto Ricans: A case for admixture-matching in clinical pharmacogenetic studies. Clin Chim Acta, 2010. 411(17-18): p. 1306–11.20488169
30 Patel, T., N. Rahimi, and M. Cassagnol, Biochemistry, Cytochrome P450, in StatPearls. 2026: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/32491630.
31 Van Booven, D., S. Marsh, H. McLeod, M.W. Carrillo, et al., Cytochrome P450 2C9-CYP2C9. Pharmacogenet Genomics, 2010. 20(4): p. 277–81.20150829
32 Gupta, A., L. Zheng, V. Ramanujam, and J. Gallagher, Novel Use of Pharmacogenetic Testing in the Identification of CYP2C9 Polymorphisms Related to NSAID-Induced Gastropathy. Pain Med, 2015. 16(5): p. 866–9.25585969
33 Sangkuhl, K., K. Claudio-Campos, L.H. Cavallari, J.A.G. Agundez, et al., PharmVar GeneFocus: CYP2C9. Clin Pharmacol Ther, 2021. 110(3): p. 662–676.34109627
34 Miners, J.O. and D.J. Birkett, Cytochrome P4502C9: an enzyme of major importance in human drug metabolism. Br J Clin Pharmacol, 1998. 45(6): p. 525–38.9663807
35 Pharmacogene Variation Consortium. PharmVar CYP2C9. 2023 22 March 2023]; Available from: https://www.pharmvar.org/gene/CYP2C9.
36 Karnes, J.H., A.E. Rettie, A.A. Somogyi, R. Huddart, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for CYP2C9 and HLA-B Genotypes and Phenytoin Dosing: 2020 Update. Clin Pharmacol Ther, 2021. 109(2): p. 302–309.32779747
37 Caudle, K.E., K. Sangkuhl, M. Whirl-Carrillo, J.J. Swen, et al., Standardizing CYP2D6 Genotype to Phenotype Translation: Consensus Recommendations from the Clinical Pharmacogenetics Implementation Consortium and Dutch Pharmacogenetics Working Group. Clin Transl Sci, 2020. 13(1): p. 116–124.31647186
38 CYP2C9 frequency table [Cited 22 March 2023]. Available from https://files.cpicpgx.org/data/report/current/frequency/CYP2C9_frequency_table.xlsx.
39 Sistonen, J., S. Fuselli, J.U. Palo, N. Chauhan, et al., Pharmacogenetic variation at CYP2C9, CYP2C19, and CYP2D6 at global and microgeographic scales. Pharmacogenetics and genomics, 2009. 19(2): p. 170–9.19151603
40 Solus, J.F., B.J. Arietta, J.R. Harris, D.P. Sexton, et al., Genetic variation in eleven phase I drug metabolism genes in an ethnically diverse population. Pharmacogenomics, 2004. 5(7): p. 895–931.15469410
41 Lee, C.R., J.A. Goldstein, and J.A. Pieper, Cytochrome P450 2C9 polymorphisms: a comprehensive review of the in-vitro and human data. Pharmacogenetics, 2002. 12(3): p. 251–63.11927841
42 CYP2C9 Allele Functionality Reference [Cited 22 March 2023]. Available from https://files.cpicpgx.org/data/report/current/allele_function_reference/CYP2C9_allele_functionality_reference.xlsx.
43 CYP2C9 Diplotype Phenotype Table [Cited 22 March 2023]. Available from https://files.cpicpgx.org/data/report/current/diplotype_phenotype/CYP2C9_Diplotype_Phenotype_Table.xlsx.
44 McDonald, M.G., M.J. Rieder, M. Nakano, C.K. Hsia, et al., CYP4F2 is a vitamin K1 oxidase: An explanation for altered warfarin dose in carriers of the V433M variant. Mol Pharmacol, 2009. 75(6): p. 1337–46.19297519
45 Zubiaur, P., C. Rodriguez-Antona, E.C. Boone, A.K. Daly, et al., PharmVar GeneFocus: CYP4F2. Clin Pharmacol Ther, 2024. 116(4): p. 963–975.39135485
46 Caldwell, M.D., T. Awad, J.A. Johnson, B.F. Gage, et al., CYP4F2 genetic variant alters required warfarin dose. Blood, 2008. 111(8): p. 4106–12.18250228
47 Sato, Y., E. Hishinuma, S. Yamazaki, A. Ueda, et al., Functional Characterization of 29 Cytochrome P450 4F2 Variants Identified in a Population of 8380 Japanese Subjects and Assessment of Arachidonic Acid omega-Hydroxylation. Drug Metab Dispos, 2023. 51(12): p. 1561–1568.37775333
48 PharmVar - CYP4F2. 2026 5 March 2026]; Available from: https://www.pharmvar.org/gene/CYP4F2.
49 Wu, Y., J. Zhao, Y. Zhao, T. Huang, et al., Genetic variants in CYP4F2 were significantly correlated with susceptibility to ischemic stroke. BMC Med Genet, 2019. 20(1): p. 155.31510945
50 Xu, J., K.A. Guertin, N.C. Gaddis, A.H. Agler, et al., Change in plasma alpha-tocopherol associations with attenuated pulmonary function decline and with CYP4F2 missense variation. Am J Clin Nutr, 2022. 115(4): p. 1205–1216.35040869
51 Perera, M.A., L.H. Cavallari, N.A. Limdi, E.R. Gamazon, et al., Genetic variants associated with warfarin dose in African-American individuals: a genome-wide association study. Lancet, 2013. 382(9894): p. 790–6.23755828
52 Singh, A., C. Alarcon, E.A. Nutescu, T.J. O'Brien, et al., Local ancestry-informed GWAS of warfarin dose requirement in African Americans identifies a CYP2C19 splicing QTL. Am J Hum Genet, 2025. 112(11): p. 2708–2719.41027428
53 Ndadza, A., S. Muyambo, P. Mntla, A. Wonkam, et al., Profiling of warfarin pharmacokinetics-associated genetic variants: Black Africans portray unique genetic markers important for an African specific warfarin pharmacogenetics-dosing algorithm. J Thromb Haemost, 2021. 19(12): p. 2957–2973.34382722
54 Sun, B., Y.F. Wen, K.A. Culhane-Pera, M. Lo, et al., Differences in Predicted Warfarin Dosing Requirements Between Hmong and East Asians Using Genotype-Based Dosing Algorithms. Pharmacotherapy, 2021. 41(3): p. 265–276.33202062
55 Nan, D., S. Li, Y. Wang, Y. Cai, et al., Quantitative Comparison of the Predictive Accuracy of Warfarin Pharmacogenetic Dosing Algorithms Derived From Population Data of Different Ethnicities in the Chinese Population. J Clin Pharmacol, 2026. 66(2): p. e70118.41044997
56 Hillman, M.A., R.A. Wilke, S.H. Yale, H.J. Vidaillet, et al., A prospective, randomized pilot trial of model-based warfarin dose initiation using CYP2C9 genotype and clinical data. Clin Med Res, 2005. 3(3): p. 137–45.16160068
57 Anderson, J.L., B.D. Horne, S.M. Stevens, A.S. Grove, et al., Randomized trial of genotype-guided versus standard warfarin dosing in patients initiating oral anticoagulation. Circulation, 2007. 116(22): p. 2563–70.17989110
58 Caraco, Y., S. Blotnick, and M. Muszkat, CYP2C9 genotype-guided warfarin prescribing enhances the efficacy and safety of anticoagulation: a prospective randomized controlled study. Clin Pharmacol Ther, 2008. 83(3): p. 460–70.17851566
59 Jonas, D.E., J.P. Evans, H.L. McLeod, S. Brode, et al., Impact of genotype-guided dosing on anticoagulation visits for adults starting warfarin: a randomized controlled trial. Pharmacogenomics, 2013. 14(13): p. 1593–603.24088130
60 Pirmohamed, M., G. Burnside, N. Eriksson, A.L. Jorgensen, et al., A randomized trial of genotype-guided dosing of warfarin. N Engl J Med, 2013. 369(24): p. 2294–303.24251363
61 Anderson, J.L., B.D. Horne, S.M. Stevens, S.C. Woller, et al., A randomized and clinical effectiveness trial comparing two pharmacogenetic algorithms and standard care for individualizing warfarin dosing (CoumaGen-II). Circulation, 2012. 125(16): p. 1997–2005.22431865
62 Syn, N.L., A.L. Wong, S.C. Lee, H.L. Teoh, et al., Genotype-guided versus traditional clinical dosing of warfarin in patients of Asian ancestry: a randomized controlled trial. BMC Med, 2018. 16(1): p. 104.29986700
63 Anand, A., N.C. Hegde, P. Chhabra, J. Purohit, et al., Pharmacogenetic guided versus standard warfarin dosing for routine clinical care with its pharmacoeconomic impact: a randomized controlled clinical trial. Ann Hematol, 2024. 103(6): p. 2133–2144.38634917
64 Guo, C., Y. Kuang, H. Zhou, H. Yuan, et al., Genotype-Guided Dosing of Warfarin in Chinese Adults: A Multicenter Randomized Clinical Trial. Circ Genom Precis Med, 2020. 13(4): p. e002602.32510984
65 Supe, S., Z. Poljakovic, T. Bozina, J. Ljevak, et al., Clinical Application of Genotype-guided Dosing of Warfarin in Patients with Acute Stroke. Arch Med Res, 2015. 46(4): p. 265–73.25989350
66 Kimmel, S.E., B. French, S.E. Kasner, J.A. Johnson, et al., A pharmacogenetic versus a clinical algorithm for warfarin dosing. N Engl J Med, 2013. 369(24): p. 2283–93.24251361
67 Makar-Ausperger, K., K. Krzelj, M. Lovric Bencic, M. Radacic Aumiler, et al., Warfarin Dosing According to the Genotype-guided Algorithm is Most Beneficial in Patients With Atrial Fibrillation: A Randomized Parallel Group Trial. Ther Drug Monit, 2018. 40(3): p. 362–368.29494423
68 Stergiopoulos, K. and D.L. Brown, Genotype-guided vs clinical dosing of warfarin and its analogues: meta-analysis of randomized clinical trials. JAMA Intern Med, 2014. 174(8): p. 1330–8.24935087
69 Tang, T., J. Liu, K. Zuo, J. Cheng, et al., Genotype-Guided Dosing of Coumarin Anticoagulants: A Meta-analysis of Randomized Controlled Trials. J Cardiovasc Pharmacol Ther, 2015. 20(4): p. 387–94.25575537
70 Franchini, M., C. Mengoli, M. Cruciani, C. Bonfanti, et al., Effects on bleeding complications of pharmacogenetic testing for initial dosing of vitamin K antagonists: a systematic review and meta-analysis. J Thromb Haemost, 2014. 12(9): p. 1480–7.25040440
71 Tse, G., M. Gong, G. Li, S.H. Wong, et al., Genotype-guided warfarin dosing vs. conventional dosing strategies: a systematic review and meta-analysis of randomized controlled trials. Br J Clin Pharmacol, 2018. 84(9): p. 1868–1882.29704269
72 Sridharan, K. and G. Sivaramakrishnan, A network meta-analysis of CYP2C9, CYP2C9 with VKORC1 and CYP2C9 with VKORC1 and CYP4F2 genotype-based warfarin dosing strategies compared to traditional. J Clin Pharm Ther, 2021. 46(3): p. 640–648.33346393
73 Wang, X., B. Tang, M. Zhou, L. Liu, et al., Efficacy and safety of genotype-guided warfarin dosing versus non-genotype-guided warfarin dosing strategies: A systematic review and meta-analysis of 27 randomized controlled trials. Thromb Res, 2022. 210: p. 42–52.34999431
74 Lee, K.E., J. Yee, G.Y. Lee, J.E. Chung, et al., Genotype-guided warfarin dosing may benefit patients with mechanical aortic valve replacements: randomized controlled study. Sci Rep, 2020. 10(1): p. 6988.32332930
75 Pengo, V., C.F. Zambon, P. Fogar, A. Padoan, et al., A Randomized Trial of Pharmacogenetic Warfarin Dosing in Naive Patients with Non-Valvular Atrial Fibrillation. PLoS One, 2015. 10(12): p. e0145318.26710337
76 de Freitas Campos, E.I., K.B. Gomes, D.D. Ribeiro, M.K. Puurunen, et al., Influence of polymorphisms in CYP2C9, VKORC1, MDR1 and APOE genes on the warfarin maintenance dose in Brazilian patients. Pharmacogenomics, 2023. 24(13): p. 701–712.37702085
77 Lee, K.J., M. Kang, E.J. Lee, J. Oh, et al., Clinical Application of Pharmacogenomics in Stroke Management: Current Evidence and Future Directions. J Stroke, 2026. 28(1): p. 58–75.41656635
78 Jokhab, S., M.M. AlRasheed, D. Bakheet, A. AlMomen, et al., The impact of CYP2C9, VKORC1, and CYP4F2 polymorphisms on warfarin dose requirement in Saudi patients. Front Pharmacol, 2025. 16: p. 1547142.40371326
79 Asiimwe, I.G., M. Blockman, L.H. Cavallari, K. Cohen, et al., Meta-analysis of genome-wide association studies of stable warfarin dose in patients of African ancestry. Blood Adv, 2024. 8(20): p. 5248–5261.39163621
80 Loebstein, R., I. Dvoskin, H. Halkin, M. Vecsler, et al., A coding VKORC1 Asp36Tyr polymorphism predisposes to warfarin resistance. Blood, 2007. 109(6): p. 2477–80.17110455
81 Rost, S., A. Fregin, V. Ivaskevicius, E. Conzelmann, et al., Mutations in VKORC1 cause warfarin resistance and multiple coagulation factor deficiency type 2. Nature, 2004. 427(6974): p. 537–41.14765194
82 Higashi, M.K., D.L. Veenstra, L.M. Kondo, A.K. Wittkowsky, et al., Association between CYP2C9 genetic variants and anticoagulation-related outcomes during warfarin therapy. JAMA, 2002. 287(13): p. 1690–8.11926893
83 Aithal, G.P., C.P. Day, P.J. Kesteven, and A.K. Daly, Association of polymorphisms in the cytochrome P450 CYP2C9 with warfarin dose requirement and risk of bleeding complications. Lancet, 1999. 353(9154): p. 717–9.10073515
84 Limdi, N.A., G. McGwin, J.A. Goldstein, T.M. Beasley, et al., Influence of CYP2C9 and VKORC1 1173C/T genotype on the risk of hemorrhagic complications in African-American and European-American patients on warfarin. Clinical pharmacology and therapeutics, 2008. 83(2): p. 312–21.17653141
85 Lindh, J.D., L. Holm, M.L. Andersson, and A. Rane, Influence of CYP2C9 genotype on warfarin dose requirements--a systematic review and meta-analysis. European journal of clinical pharmacology, 2009. 65(4): p. 365–75.19031075
86 Mizzi, C., E. Dalabira, J. Kumuthini, N. Dzimiri, et al., A European Spectrum of Pharmacogenomic Biomarkers: Implications for Clinical Pharmacogenomics. PLoS One, 2016. 11(9): p. e0162866.27636550
87 Johnson, J.A., L. Gong, M. Whirl-Carrillo, B.F. Gage, et al., Clinical Pharmacogenetics Implementation Consortium Guidelines for CYP2C9 and VKORC1 genotypes and warfarin dosing. Clinical pharmacology and therapeutics, 2011. 90(4): p. 625–9.21900891
88 Shendre, A., C. Dillon, and N.A. Limdi, Pharmacogenetics of warfarin dosing in patients of African and European ancestry. Pharmacogenomics, 2018. 19(17): p. 1357–1371.30345882
89 MM, M.H., Z. Chikwambi, G. Ngwende, J.A. Matenga, et al., Warfarin pharmacogenetics in a black Zimbabwean cohort: an observational prospective study. Pharmacogenomics, 2023. 24(10): p. 529–538.37435666
90 Wang, D., D.P. Dai, H. Wu, J. Chong, et al., Effects of rare CYP2C9 alleles on stable warfarin doses in Chinese Han patients with atrial fibrillation. Pharmacogenomics, 2020. 21(14): p. 1021–1031.32893731
91 Claudio-Campos, K., M. Monero-Paredes, E. Hernandez, J. Renta, et al., Low-frequency variants at the CYP2C9 locus among Puerto Rican patients on warfarin: in silico predictions of functionality and conservation. Pharmacogenomics, 2019. 20(12): p. 891–902.31453773
92 Claudio-Campos, K.I., P. Gonzalez-Santiago, J.Y. Renta, J. Rodriguez, et al., CYP2C9*61, a rare missense variant identified in a Puerto Rican patient with low warfarin dose requirements. Pharmacogenomics, 2019. 20(1): p. 3–8.30518301
93 Reyes-Gonzalez, S., C. de Las Barreras, G. Reynaldo, L. Rodriguez-Vera, et al., Genotype-driven pharmacokinetic simulations of warfarin levels in Puerto Ricans. Drug Metab Pers Ther, 2020. 35(4).34704696
94 Martinez-Jimenez, J.E., Y. Ortega-Lampon, D. Cedres-Rivera, F. Heredia-Negron, et al., Leveraging Machine Learning to Predict Warfarin Sensitivity in the Puerto Rican Population: A Pharmacogenomic Approach. Int J Environ Res Public Health, 2026. 23(3).41899714
95 Kumondai, M., A. Ito, E.M. Gutierrez Rico, E. Hishinuma, et al., Functional Assessment of 12 Rare Allelic CYP2C9 Variants Identified in a Population of 4773 Japanese Individuals. J Pers Med, 2021. 11(2).33540768
96 Danese, E., M. Montagnana, J.A. Johnson, A.E. Rettie, et al., Impact of the CYP4F2 p.V433M polymorphism on coumarin dose requirement: systematic review and meta-analysis. Clin Pharmacol Ther, 2012. 92(6): p. 746–56.23132553
97 Liang, R., C. Wang, H. Zhao, J. Huang, et al., Influence of CYP4F2 genotype on warfarin dose requirement-a systematic review and meta-analysis. Thromb Res, 2012. 130(1): p. 38–44.22192158
98 Asiimwe, I.G., M. Blockman, K. Cohen, C. Cupido, et al., A genome-wide association study of plasma concentrations of warfarin enantiomers and metabolites in sub-Saharan black-African patients. Front Pharmacol, 2022. 13: p. 967082.36210801
99 Verhoef, T.I., W.K. Redekop, A.K. Daly, R.M. van Schie, et al., Pharmacogenetic-guided dosing of coumarin anticoagulants: algorithms for warfarin, acenocoumarol and phenprocoumon. Br J Clin Pharmacol, 2014. 77(4): p. 626–41.23919835
100 Gurbel, P.A., K. Bliden, M. Sherwood, H. Taheri, et al., Development of a routine bedside CYP2C19 genotype assessment program for antiplatelet therapy guidance in a community hospital catheterization laboratory. J Thromb Thrombolysis, 2024. 57(4): p. 566–575.38480590
101 Abdel-Latif, R., W. Al Muftah, S. Mohammed, T. AlHsson, et al., Implementing CYP2C19 Pharmacogenetic Testing for Personalized Antiplatelet Therapy: Findings From the QPGx-CARES Initiative. Clin Ther, 2026. 48(2): p. 170–178.41455673
102 Burke, K.A., J. O'Sullivan, N. Godfrey, V. Sharma, et al., Development and Validation of a Rapid Point-of-Care CYP2C19 Genotyping Platform. J Mol Diagn, 2025. 27(3): p. 209–215.39725012
103 Leach, M., W.G. Newman, and J.H. McDermott, Rapid point of care testing: the next frontier in pharmacogenomics. Pharmacogenomics, 2024. 25(7): p. 289–291.39041736
104 Liu, E.P., Y. Wang, X.H. He, J.J. Guan, et al., Whole Blood PCR Amplification with Pfu DNA Polymerase and Its Application in Single-Nucleotide Polymorphism Analysis. Genet Test Mol Biomarkers, 2015. 19(11): p. 610–6.26360116
105 Jorgensen, A.L., C. Prince, G. Fitzgerald, A. Hanson, et al., Implementation of genotype-guided dosing of warfarin with point-of-care genetic testing in three UK clinics: a matched cohort study. BMC Med, 2019. 17(1): p. 76.30961588
106 Tomlinson, E., C. Cooper, H.E. Jones, C.L. Manzano, et al., Accuracy and technical characteristics of CYP2C19 point of care tests: a systematic review. Pharmacogenomics, 2024. 25(8-9): p. 407–423.39229818
107 Larkins, M.C., M. Zubair, and A. Thombare, Point-of-Care Testing, in StatPearls. 2026: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/37276307.
108 Scott, S.A., Clinical pharmacogenomics: opportunities and challenges at point of care. Clin Pharmacol Ther, 2013. 93(1): p. 33–5.23212102
109 Nagai, R., M. Ohara, L.H. Cavallari, K. Drozda, et al., Factors influencing pharmacokinetics of warfarin in African-Americans: implications for pharmacogenetic dosing algorithms. Pharmacogenomics, 2015. 16(3): p. 217–25.25712185
110 Bress, A., S.R. Patel, M.A. Perera, R.T. Campbell, et al., Effect of NQO1 and CYP4F2 genotypes on warfarin dose requirements in Hispanic-Americans and African-Americans. Pharmacogenomics, 2012. 13(16): p. 1925–35.23215885
111 Hernandez-Suarez, D.F., K. Claudio-Campos, J.E. Mirabal-Arroyo, B.A. Torres-Hernandez, et al., Potential of a Pharmacogenetic-Guided Algorithm to Predict Optimal Warfarin Dosing in a High-Risk Hispanic Patient: Role of a Novel NQO1*2 Polymorphism. J Investig Med High Impact Case Rep, 2016. 4(4): p. 2324709616682049.28210634
112 El Rouby, N., L. Rodrigues Marcatto, K. Claudio, L. Camargo Tavares, et al., Multi-site Investigation of Genetic Determinants of Warfarin Dose Variability in Latinos. Clin Transl Sci, 2021. 14(1): p. 268–276.32860733
113 Ramirez, A.H., Y. Shi, J.S. Schildcrout, J.T. Delaney, et al., Predicting warfarin dosage in European-Americans and African-Americans using DNA samples linked to an electronic health record. Pharmacogenomics, 2012. 13(4): p. 407–18.22329724
114 Furie, B., Do pharmacogenetics have a role in the dosing of vitamin K antagonists? N Engl J Med, 2013. 369(24): p. 2345–6.24251364
115 Finkelman, B.S., B. French, L. Bershaw, and S.E. Kimmel, Factors affecting time to maintenance dose in patients initiating warfarin. Pharmacoepidemiol Drug Saf, 2015. 24(3): p. 228–36.25504915
116 Belley-Cote, E.P., H. Hanif, F. D'Aragon, J.W. Eikelboom, et al., Genotype-guided versus standard vitamin K antagonist dosing algorithms in patients initiating anticoagulation. A systematic review and meta-analysis. Thromb Haemost, 2015. 114(4): p. 768–77.26158747
117 Verschuren, J.J., S. Trompet, J.A. Wessels, H.J. Guchelaar, et al., A systematic review on pharmacogenetics in cardiovascular disease: is it ready for clinical application? Eur Heart J, 2012. 33(2): p. 165–75.21804109
118 Gage, B.F., A.R. Bass, H. Lin, S.C. Woller, et al., Effect of Genotype-Guided Warfarin Dosing on Clinical Events and Anticoagulation Control Among Patients Undergoing Hip or Knee Arthroplasty: The GIFT Randomized Clinical Trial. JAMA, 2017. 318(12): p. 1115–1124.28973620
119 Kim, K., J.D. Duarte, W.L. Galanter, J. Han, et al., Pharmacist-guided pharmacogenetic service lowered warfarin-related hospitalizations. Pharmacogenomics, 2023. 24(6): p. 303–314.37166395
120 Kalman, L.V., J. Agundez, M.L. Appell, J.L. Black, et al., Pharmacogenetic allele nomenclature: International workgroup recommendations for test result reporting. Clin Pharmacol Ther, 2016. 99(2): p. 172–85.26479518
121 Gaedigk, A., M. Ingelman-Sundberg, N.A. Miller, J.S. Leeder, et al., The Pharmacogene Variation (PharmVar) Consortium: Incorporation of the Human Cytochrome P450 (CYP) Allele Nomenclature Database. Clin Pharmacol Ther, 2018. 103(3): p. 399–401.29134625

Figure 1.

The CPIC (2017) Dosing Recommendations for Warfarin Dosing based on Genotype for Adults. (a) “Dose clinically” means to dose without genetic information, which may include use of a clinical dosing algorithm or standard dose approach. (b) Data strongest for European and East Asian ancestry populations and consistent in other populations. (c) 45–50% of individuals with self‐reported African ancestry have CYP2C9*5, *6, *8, *11, or rs12777823. If CYP2C9*5, *6, *8, and *11 were not tested, dose warfarin clinically. Note: these data derive primarily from African Americans, who are largely from West Africa. It is unknown if the same associations are present for those from other parts of Africa. (d) Most algorithms are developed for the target INR 2‐3. (e) Consider an alternative agent in individuals with genotypes associated with CYP2C9 poor metabolism (namely, CYP2C9*3/*3, *2/*3, *3/*3) or both increased sensitivity (VKORC1 A/G or A/A) and CYP2C9 poor metabolism. (f) See the EU‐PACT trial for pharmacogenetics‐based warfarin initiation (loading) dose algorithm with the caveat that the loading dose algorithm has not been specifically tested or validated in populations of African ancestry. (g) Larger dose reduction might be needed in variant homozygotes (20–40%). (h) African American refers to individuals mainly originating from West Africa. This figure is adapted from (2). Please see Therapeutic Recommendations based on Genotype for more information from CPIC.

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug. Certain terms, genes, and genetic variants may be corrected in accordance with nomenclature standards, where necessary. We have given the full name of abbreviations, shown in square brackets, where necessary.