# Venlafaxine Therapy and CYP2D6 Genotype

## Introduction

Venlafaxine (brand name Effexor) is an antidepressant used in the treatment of major depressive disorder, anxiety, and panic disorders. Venlafaxine belongs to the drug class of serotonin and norepinephrine reuptake inhibitors (SNRIs), as does its major metabolite, O-desmethylvenlafaxine, also called desvenlafaxine (brand name Pristiq).

Venlafaxine is metabolized into its major active metabolite, O-desmethylvenlafaxine (ODV), primarily by the CYP2D6 enzyme. As such, individuals that have high plasma concentrations of venlafaxine and low plasma concentrations of ODV when taking venlafaxine, indicates they have reduced or absent CYP2D6 activity. Reduced or absent CYP2D6 activity can result from genetic variation or from concomitant use of medications that inhibit the CYP2D6 enzyme. Individuals who have genetic variants associated with no enzyme activity are called “CYP2D6 poor metabolizers” (PM) and account for approximately 7% of indviduals of European ancestry.

The FDA-approved drug label for venlafaxine does not provide specific dose adjustments for CYP2D6 PM, though the FDA Table of Pharmacogenetic Associations states that a dose reduction can be considered. The labeling further states that no dose adjustment is required when venlafaxine is coadministered with a CYP2D6 inhibitor, though the other medication may require adjustment (Table 1) (1, 2). The label states that although imipramine (an antidepressant that inhibits CYP2D6) was found to partially inhibit venlafaxine metabolism, the total concentration of active compounds (venlafaxine plus ODV) was not affected. In addition, the label cites a clinical study comparing venlafaxine use in CYP2D6 PM and normal metabolizers (NM), which found that the total concentration of active compounds (venlafaxine plus ODV) was similar in both metabolizer groups.

The Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Association for the Advancement of Pharmacy has published venlafaxine dosing recommendations based on CYP2D6 genotype. These recommendations are not based on differences in the total concentration of active compounds (venlafaxine plus ODV), but on findings that low ODV/venlafaxine ratios (as occur in CYP2D6 PM and intermediate metabolizers (IM)) result in a decrease in both the chance that venlafaxine is effective and the chance that venlafaxine is well tolerated. Because dose adjustments do not change the ODV/venlafaxine ratios, for CYP2D6 PM and intermediate metabolizers (IM), DPWG recommends that an alternative drug is used. If an alternative medication is not an option and side effects occur, DPWG recommends a venlafaxine dose reduction based on clinical response and drug levels, but warns that it is not known whether it is possible to reduce the dose to such an extent that side effects disappear, while effectiveness is maintained (Table 2). For individuals with increased CYP2D6 activity, ultrarapid metabolizers (UM), who have high ODV/venlafaxine ratios, studies did not show a decrease in effectiveness or increase in side effects. In addition, there was only a slight decrease in active moiety exposure. For these reasons, DPWG guidelines state that this decrease is low relative to the therapeutic window for venlafaxine and thus do not recommend dose therapy adjustment for UM individuals (3).

Guidelines from the Clinical Pharmacogenetics Implementation Consortium (CPIC) published in 2023 provide an optional recommendation to avoid venlafaxine in CYP2D6 PM individuals but did not find sufficient clinical evidence to alter dosing on the basis of CYP2D6 activity for any other phenotype (Table 3) (4).

Table 1.

Venlafaxine and CYP2D6 Recommendations (FDA, 2024)

CYP2D6 status | Clinical impact | Recommendation
CYP2D6 PM | Increased levels of venlafaxine and reduced levels of ODV compared with people with normal CYP2D6 levels | Consider dosage reductions.^1^
CYP2D6 substrate comedications | Increased exposure (C_max_ and AUC) of CYP2D6 substrate medication, may increase risk of toxicity of the CYP2D6 substrate | No change in venlafaxine therapy, consider reduction in concomitant CYP2D6 substrates.

PM- poor metabolizer; C_max_- Maximum plasma concentration; AUC- Area under the curve, total plasma concentration over time.

^1^ This text specifically drawn from Section 1 of the US Food and Drug Administration Table of Pharmacogenetics Associations.

This table is adapted from (1, 2).

Table 2.

Therapeutic Recommendations for CYP2D6 and Venlafaxine (DPWG, 2024)

Phenotype | Recommendation
CYP2D6 PM | Avoid venlafaxine^1^ If it is not possible to avoid venlafaxine and side effects occur: reduce the dose; monitor the effect and side effects or check the plasma concentrations of venlafaxine and O-desmethylvenlafaxine^2,3^
CYP2D6 IM | Avoid venlafaxine^1^ If it is not possible to avoid venlafaxine and side effects occur: reduce the dose; monitor the effect and side effects or check the plasma concentrations of venlafaxine and O-desmethylvenlafaxine^2^

^1^ Antidepressants that are not metabolized by CYP2D6 –– or to a lesser extent –– include, for example, duloxetine, mirtazapine, (es)citalopram, and sertraline

^2^ It is not known whether it is possible to reduce the dose to such an extent that the side effects disappear, while the effectiveness is maintained. In general, it is assumed that the effectiveness is determined by the sum of the plasma concentrations of venlafaxine and O-desmethylvenlafaxine. However, the side effects do not appear to be related to this sum.

^3^ Furthermore, a reduced effectiveness of venlafaxine has been observed in individuals with depression having this gene variation.

PM- poor metabolizer, IM- intermediate metabolizer (activity reduced relative to normal, but not absent)

This table is adapted from (3).

Table 3.

Therapeutic Recommendations for CYP2D6 and Venlafaxine (CPIC, 2023)

Phenotype | Implication | Recommendation
CYP2D6 PM | Decreased metabolism of venlafaxine to active metabolite O-desmethylvenlafaxine and decreased O-desmethylvenlafaxine:venlafaxine ratio; The clinical impact is unclear, but CYP2D6 PM genotype has been associated with adverse effects | Consider a clinically appropriate alternative antidepressant not predominantly metabolized by CYP2D6 (Optional recommendation)
CYP2D6 IM | Decreased metabolism of venlafaxine to active metabolite O-desmethylvenlafaxine and decreased O-desmethylvenlafaxine:venlafaxine ratio; insufficient evidence for clinical impact. | No action recommended.
CYP2D6 UM | Increased metabolism of venlafaxine to the active metabolite O-desmethylvenlafaxine and increased O-desmethylvenlafaxine: venlafaxine ratio; insufficient evidence for clinical impact. | No action recommended.

UM- ultrarapid metabolizer; IM- intermediate metabolizer (activity reduced relative to normal, but not absent); PM- poor metabolizer.

Table adapted from (4).

## Drug: Venlafaxine

Venlafaxine is an antidepressant used in the treatment of major depressive disorder, generalized anxiety disorder, social anxiety disorder, and panic disorder in adults; however, it is not approved for use in pedatric individuals (1). An off-label use of venlafaxine is in the management of post-traumatic stress disorder (1, 5). Additionally, there is a black box warning from the FDA-approved labelling regarding an increased risk of suicidal thoughts and behavior in young adults taking antidepressants, which warrants close monitoring for worsening or emergence of suicidal thoughts or behaviors (1).

Venlafaxine is thought to exert its antidepressant effect by blocking the transporter reuptake proteins for key neurotransmitters affecting mood, thereby leaving more active neurotransmitters in the synapse. This is known as the “potentiation of neurotransmission.”

Venlafaxine belongs to the drug class of serotonin-norepinephrine reuptake inhibitors (SNRIs). Other drugs with SNRI activity include atomoxetine (used in the treatment of ADHD) and tramadol (an analgesic). However, because venlafaxine also weakly inhibits dopamine reuptake, it is also classified as a serotonin-norepinephrine-dopamine reuptake inhibitor (SNDRI).

The toxicity of venlafaxine appears to be higher than for other drugs of the same class. Side effects include an increase in anxiety, insomnia, and nervousness; the precipitation of mania or hypomania in individuals with bipolar disorder; as well as weight loss, reduced appetite, hyponatremia, seizures, cardiac conduction abnormalities, and an increased risk of bleeding events. There is also a risk of discontinuation syndrome, which may occur if venlafaxine therapy is stopped abruptly or if the dose is reduced. Symptoms include agitation, anorexia, anxiety, and confusion. A gradual reduction in the dose of venlafaxine is recommended, whenever possible (1, 6).

Venlafaxine is metabolized in the liver to its major active metabolite, ODV. Venlafaxine and ODV share similar activity, and ODV is also an FDA-licensed antidepressant (desvenlafaxine). The formation of ODV is catalyzed by the enzyme CYP2D6. Individuals who lack CYP2D6 activity (CYP2D6 PM) have a higher ratio of venlafaxine to ODV compared with normal metabolizers. As such, a venlafaxine:ODV ratio greater than one strongly predicts individuals who are CYP2D6 PM (7). Other hepatic enzymes (CYP3A4, CYP2C19, and CYP2C9) also contribute—to a lesser extent—to the metabolism of venlafaxine and ODV to minor, less active metabolites (8). There is evidence that CYP2D6 has enantiomeric selectivity for R-(-)- versus S-(+)-venlafaxine, resulting in a more rapid conversion to R-(-)-ODV which is more pronounced in CYP2D6 IM individuals (9, 10).

The FDA-approved drug labels for venlafaxine and venlafaxine extended release formulation both state that although CYP2D6-mediated metabolism is impacted both by genetic PM status and co-medication with inhibitors, the sum of venlafaxine and ODV is similar in both normal and reduced CYP2D6 activity individuals (1, 11). The drug label approved by Health Canada similarly acknowledges the drug-gene interaction but states that no dosage adjustment is needed (12). The guidance on the FDA Table of Pharmacogenetic Associations says that for CYP2D6 PM individuals, one can consider a dose reduction for venlafaxine therapy (2). Recommendations from the DPWG state that for poor and intermediate metabolizers, there is insufficient data to calculate the dose adjustment for venlafaxine and an alternative drug should be used (for example, citalopram, duloxetine, mirtazapine, or sertraline). If an alternative medication is not an option and side effects occur, DPWG recommends a venlafaxine dose reduction based on clinical response, and venlafaxine and ODV plasma level monitoring, but warns that it is not known whether it is possible to reduce the dose to such an extent that side effects disappear, while effectiveness is maintained (3). Similarly, CPIC recommends consideration of an alternate medication for CYP2D6 PM; however, this is an optional recommendation (4).

The FDA approved label says geriatric individuals are more likely to experience hyponatremia side effects with venlafaxine therapy (1). Dose-adjusted plasma concentrations (C/D) of venlafaxine were found to increase with age in a large cohort (5,869 individuals) of therapeutic drug monitoring samples in Norway, with individuals aged 25 to 50 showing similar plasma C/D but individuals aged 86 or older were observed, on average, to have double the C/D of the younger individuals; the increase in C/D ratio was noted to begin at an earlier age for women than men (13).

Venlafaxine is not approved by the FDA for pediatric use as safety and efficacy have not been established for this population (1). Clinical trials in pediatric individuals reported weight loss of at least 3.5%, with additional studies showing individuals under 12 years of age having more significant differences in weight gain than those over 12 years of age (11). There was also a high rate of suicidal ideation in pediatric individuals associated with venlafaxine use more so than other age groups (1).

The FDA-approved drug label states that venlafaxine should be used in pregnancy only if clearly needed (11). Risks associated with venlafaxine therapy during gestation and pregnancy include an almost 2-fold increase in risk of postpartum hemorrhage and possible risk of preeclampsia for the mother; neonates with in utero exposure may require prolonged hospitalization, respiratory support, and tube feeding (1). These should be weighed against the risks associated with untreated depression during pregnancy and increased likelihood of maternal depression relapse if antidepressant therapy is discontinued (1). Given the role of CYP enzymes in the metabolism of venlafaxine, some groups have studied the levels of venlafaxine and ODV over the course of pregnancy and the associated changes in CYP activity. One analysis of this data reported that pregnant women with NM or UM CYP2D6 phenotypes may experience subtherapeutic plasma levels at standard dosing; for NMs the risk is 90% or more after 25 weeks of gestation in a pharmakokinetic model that validated against the limited literature on venlafaxine in pregnancy. Approximately 90% of pregnant females who are UM are at risk of subtherapeutic levels at baseline, by 25 weeks gestation this rises to 98%. (14)

Venlafaxine and ODV have been detected in human breast milk, but adverse effects in breastfed infants have not been frequently observed (1, 15). Breastfed infants, especially newborn or preterm infants, may require monitoring for excessive sedation and to confirm there is adequate weight gain if maternal venlafaxine use is continued (15). There may be some clinical benefit to infants experiencing venlafaxine withdrawal to continue receiving breastmilk with venlafaxine and metabolites, as it can mitigate withdrawal symptoms (15). A physiologically based pharmacokinetic model describing metabolism and exposure of venlafaxine and ODV were developed for lactating mothers and breastfed infants (16). The model, based on existing models and simulations, also included data from two small clinical studies of breastfeeding mothers and their infants. The authors reported the modeled variation in relative infant daily dose was inversely correlated with activity levels of CYP2D6, CYP2C9 and CYP2C19, with higher relative doses being observed in association with PM status for these enzymes, though the combined exposure for both venlafaxine and ODV were below the thresholds reported for adverse events in adults and children (16).

## Gene: CYP2D6

The CYP450 family is a large and diverse group of enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs in the liver. The CYP450 genes are highly polymorphic and can result in decreased, absent, or increased enzyme activity. One prominent cytochrome P450 member, CYP2D6, is responsible for metabolizing many commonly prescribed drugs, including antidepressants, antipsychotics, analgesics, and beta-blockers.

### The CYP2D6 Alleles

The CYP2D6 gene is highly polymorphic, with over 180 star (*) alleles described and cataloged by the Pharmacogene Variation (PharmVar) Consortium. Each allele is associated with either normal, decreased, or absent enzyme function (Table 4) (17, 18). Star alleles are defined by the variants detected on one chromosome (haplotype).

The combination of CYP2D6 haplotypes a person has determines their diplotype (for example, CYP2D6 *4/*4). Based on their impact on enzyme function, each allele is assigned an activity score from 0 to 1, which in turn is then used to assign a phenotype of metabolizer status (for example, CYP2D6 PM). However, the activity score system is not standardized across all clinical laboratories or genotyping platforms, leading to variability in results. To address this, the CPIC and DPWG have created a consensus activity score guideline for CYP2D6 phenotype. The CYP2D6 phenotype is predicted from the diplotype activity score, calculated as the sum of the allele score values, including deletions or duplications, which usually ranges from 0 to 3.0: (19)

● An ultrarapid metabolizer (UM) has an activity score greater than 2.25

● A normal metabolizer (NM) has an activity score of 1.25–2.25

● An intermediate metabolizer (IM) has an activity score of >0–<1.25

● A PM has an activity score of 0

Table 4.

Activity Status of Selected CYP2D6 Alleles

Allele type | CYP2D6 alleles | Activity score
Normal function | *1, *2, *34, *39 | 1
Decreased function | *14, *17, *29, *49 | 0.5
Strongly Decreased function | *9, *10, *41 | 0.25
No function | *3, *4, *5, *6, *36 | 0

For a comprehensive list of CYP2D6 alleles, please See the Pharmacogene Variation Consortium (https://www.pharmvar.org/gene/CYP2D6) and (18). Activity scores from (20).

The CYP2D6*1 allele is the wild-type allele, when no variants are detected, and it is associated with normal enzyme activity and the NM phenotype. As the *1 allele is the default when no variants are detected, the variants interrogated prior to assigning a *1 haplotype are very important to define (see Genetic Testing section below). The CYP2D6*2, *27, and *33 alleles are also considered to have near-normal activity.

Other CYP2D6 alleles include variants that produce a non-functioning enzyme (for example, *3, *4, and *6) (21, 22) or an enzyme with decreased activity (for example, *10, *17, and *41) (18, 23) (see Table 4). There are significant inter-ethnic differences in the frequency of these alleles. For instance, *3, *4, *6, and *41 are more common in individuals with European ancestry, *17 is more frequent in individuals of African ancestry, and *10 is prevalent in those of Asian ancestry. (24)

Larger structural variants at the CYP2D6 locus have also been described, including gene duplications, deletions, tandem alleles, gene hybrids (namely, CYP2D6-CYP2D7), and gene conversions. As expected, deletions result in a no-function allele (for example, the CYP2D6*5 allele is a deletion). Duplications have been reported for alleles with normal function and decreased function. In the case of allele duplications, the activity scores for the full complement of CYP2D6 alleles are summed to determine the predicted metabolizer phenotype. Additional details on structural variants are available from PharmVar (see the document Structural Variation for CYP2D6) (25).

The frequency of the CYP2D6 star alleles with altered function varies across global populations, resulting in different frequencies of the resulting metabolizer phenotype. Given CYP2D6’s role in the metabolism of many drugs, the literature on allele and phenotype frequency is expansive. Most populations have a high frequency for normal-function star alleles, resulting in a large proportion of individuals classified as NMs; however, decreased-function alleles like CYP2D6*10 are highly prevalent in East Asian populations, resulting in a higher proportion of IM phenotype individuals in this ancestral group. Many groups in sub-Saharan Africa have higher frequencies of decreased-function alleles like CYP2D6*17 and *29, which are associated with lower metabolizer scores in these individuals.

The frequency of UM phenotypes is notably high in certain regions, including northern Africa, (particularly Algeria), the mestizo Columbian population, the Druze ancestry group from the Middle East, and non-Austronesian Melanesian populations (26, 27). Given the distribution of duplicated, functional CYP2D6 alleles, it has been proposed that a gene duplication event arose in populations based in the region of Saudi Arabia-Ethiopia, then spread through migration along the Mediterranean, resulting in a higher frequency of UM phenotype in the ancestral populations from these regions (28, 29).

More detailed information on published allele and phenotype frequencies can be found in the CYP2D6 supplemental chapter.

Pharmacologic Conversion of CYP2D6 Phenotype

Factors other than genotype can affect CYP enzyme activity and, consequently, an individual’s metabolizer phenotype. Administration of an interacting medication can lead to a phenomenon called phenoconversion, in which a genotype-based metabolizer status is altered due to concomitant enzyme inhibition or activation. Published data indicate that 17–25% of individuals are impacted by phenoconversion (30).

The enzymatic activity of CYP2D6 can be inhibited or reduced by medications including, but not limited to strong inhibitors such as paroxetine, fluoxetine, bupropion, and quinidine, as well as moderate inhibitors like duloxetine (31, 32). This inhibition can result in UMs, NMs or IMs responding to medications as if they were PMs, depending upon the strength of the enzyme inhibition. Strong inhibitors can completely inhibit CYP2D6, while moderate inhibitors can reduce activity by 50%. Co-medication with multiple strong or moderate CYP2D6 inhibitors may result in reduced metabolism of drug substrates, a phenomenon commonly observed in psychiatric pharmacotherapy (33, 34). There are no known inducers of CYP2D6 activity.

Conversely, discontinuing a CYP2D6 inhibitor can revert an individual's CYP2D6 activity to their genetically predicted phenotype baseline. Integration of CYP2D6 phenoconversion into clinical practice requires knowledge of multiple clinical factors, and tools have been developed to support clinicians (35).

Other Genes of Interest:

Regarding venlafaxine phamacokinetics and pharmacodynamics, multiple additional genes have been studied as potential factors contributing to efficacy and adverse effects. The P-glycoprotein (P-gp) transporter protein (encoded by ABCB1) mediates transport of substrates against their concentration gradient and exchange between tissues and the bloodstream. Alterations in P-gp due to variation of ABCB1 may impact therapeutic response and side effects of antidepressants and other medications. Individuals with a TT genotype at rs1045642 (ABCB1 c.3435C>T) or the TT/TA genotypes at rs2032582 (ABCB1 c.2677G>T/A) had a higher frequency of venlafaxine-induced akathisia; no effect was observed on efficacy (36). This evidence was not sufficient to warrant genotype-guided dosing recommendations from CPIC (4).

Other CYP enzymes are involved in venlafaxine metabolism and have been studied as potential contributors to exposure and treatment response. Individuals with CYP2C19 rapid (RM) or ultrarapid metabolism (UM) had lower dose-corrected plasma levels of venlafaxine compared with CYP2C19 IM, which has prompted one author group to propose inclusion of CYP2C19 genotyping for venlafaxine-treated individuals. Scherf-Clavel and colleagues state this may improve therapy outcomes by alerting clinicians to the risk of low serum concentrations and non-response in CYP2C19 RM or UM individuals, (37) though CPIC did not find enough evidence to warrant a recommendation based on CYP2C19 (4).

## Linking CYP2D6 Genetic Variation with Treatment Response

An individual’s CYP2D6 status may influence their risk of side effects from venlafaxine therapy. Individuals who are CYP2D6 PM have increased levels of venlafaxine and decreased levels of ODV –– this appears to translate into a higher risk of side effects and a reduced response to therapy (38). In addition, in individuals who failed another antidepressant therapy, CYP2D6 UM were more likely to achieve depression remission than PMs when treated with venlafaxine (39). This trend was also observed in a Japanese study cohort, with the ODV/VEN ratio decreasing as the number of decreased function CYP2D6 alleles (namely, CYP2D6*5 or *10) increased (40). Older indivduals may be particularly at risk (41, 42, 43). However, in vitro analyses have suggested that different reduced-function CYP2D6 alleles may have differing degrees of reduced activity toward venlafaxine due to substrate specificity (44).

Side effects reported to occur more frequently in PMs receiving venlafaxine include gastrointestinal side effects, such as vomiting and diarrhea; and cardiovascular side effects, such as hypertension, tachycardia, and prolonged QTc interval (45, 46). Additionally, diabetic CYP2D6 PMs had an average higher level of HBA1c compared with NM, indicating worse blood sugar control in these individuals (47).

Performing CYP2D6 genotyping prior to starting venlafaxine therapy would enable personalized dosing, which in combination with therapeutic drug monitoring, could reduce the time taken before an adequate maintenance dose is established, and prevent potential side effects (8, 43, 45, 48, 49, 50). However, evidence for the benefits of routine CYP2D6 genotyping is mixed. Multiple studies report that the metabolic changes associated with CYP2D6 variants do not have a sufficient effect on venlafaxine therapeutic levels, and that CYP2D6 genotyping would not predict the efficacy of venlafaxine in indivduals with depression (51, 52, 53, 54, 55). One study of older adults indicated that CYP2D6 PMs experienced higher exposure to venlafaxine and its active metabolite, putting them at risk for concentration-dependent adverse effects (56).

Concomitant use of CYP2D6 inhibitors and other conditions (also called comorbidities) have been shown to alter the ratio of venlafaxine to ODV due to phenoconversion. Bupropion inhibited CYP2D6 activity in NM individuals leading to phenoconversion to PM in 19% of individuals taking 150 mg/d and 50% of indivividuals taking 300mg/d or greater (57). Physiologically based pharmacokinetic modeling of this drug-drug-gene interaction further supports an increased in venlafaxine exposure with increasing bupropion dose, though the total active moiety (venlafaxine plus ODV) exposure is not significantly different (58). Disease-induced phenoconversion (due to cancer) was reported in an individual with a genotype consistent with CYP2D6 IM, but who had a low ODV/VEN ratio consistent with PM phenotype (59). Additional medications, supplements, or botanical extracts may also cause phenoconversion, given documented interaction between herbal medicines or supplements with venlafaxine/ODV ratios and metabolism (60, 61). Physiologically based pharmacokinetic models have been developed to account for drug-drug interactions, CYP2D6 metabolizer status, and pregnancy (14, 62, 63).

## Genetic Testing

The NIH’s Genetic Testing Registry provides examples of the genetic tests that are available for venlafaxine response (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN078028) and for the CYP2D6 gene (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1565%5Bgeneid%5D). The available CYP2D6 tests include targeted single-gene tests as well as multi-gene panels. In addition, variant CYP2D6 alleles to be included in clinical genotyping assays have been recommended by the Association for Molecular Pathology (AMP) (64). For CYP2D6, the AMP recommends that the minimum panel of variant alleles include *2, *3, *4, *5, *6, *9, *10, *17, *29, *41 and copy number interrogation.

The CYP2D6 gene is difficult to genotype due to the large number of variants, including structural variants, and the presence of homologous pseudogenes. The complexity of genetic variation complicates making a correct determination of CYP2D6 genotype. Typically, the *1 allele is reported if no variants are detected, thus it is important to consider what alleles and what types of variants are detected by the test when evaluating the results of any individual report.

Results are typically reported as a diplotype, such as CYP2D6 *1/*1 (wild-type). A copy number result, if available, is also important when interpreting CYP2D6 results (65, 66). When individuals have more than 2 copies of CYP2D6, the copies of the allele are denoted by “xN”, where the “N” can either be quantified or unquantified (for example, CYP2D6*1/*2x2 or CYP2D6 *1/*2xN). Some laboratories also use the notation of “DUP” to indicate an increase in copy number, but the report does not always specify the number of duplications or the allele that has been duplicated due to technical limitations. The test results may include an interpretation of the individual’s predicted metabolizer phenotype, which can be confirmed by checking the diplotype and calculating the CYP2D6 activity score, as described in the “CYP2D6 Alleles” section above. Additional tools are also available to assist with genotype to phenotype interpretation (PharmCAT (https://pharmcat.clinpgx.org/)) and retrieval of guidelines based on the reported genotype (Genotype Selection Interface (https://www.clinpgx.org/genotype) or PharmDOG (https://pharmdog.clinpgx.org/genotypes)).

Multiple studies have reported successful implementation of pharmacogenetic testing to guide medication selection or dosing in a real-world clinical setting (67, 68, 69). Of particular concern are cases where individuals are prescribed multiple medications for chronic health conditions, as gene-drug or gene-drug-drug interactions may negatively impact the individual’s response to medications (70).

## The CYP2D6 Gene Interactions with Medications Used for Additional Indications

The CYP family of enzymes is involved in the metabolism of many substances and CYP2D6 especially has been implicated in altered pharmacologic responses for many compounds. The drugs can be categorized into many different classes:

- Antipsychotics—for example, aripiprazole, risperidone, thioridazine and—to a lesser extent—clozapine are metabolized by CYP2D6. According to the FDA, aripiprazole dosage should be reduced for PMs and thioridazine is contraindicated for individuals who are known to have reduced CYP2D6 activity due to increased risk of potentially fatal side effects. The UMs may have a decreased plasma concentration of risperidone, per DPWG recommendations.
- Cardiovascular diseases—for example, metoprolol, carvedilol, and propafenone are used to manage arrhythmias or heart failure and changes in CYP2D6 activity can impact the levels of these medications.
- Tricyclic antidepressants—for example, amitriptyline, and imipramine may require dosage adjustments, potentially guided by therapeutic drug monitoring, to achieve the desired therapeutic range in ultrarapid (UMs) or PMs. Ultimately, tricyclic antidepressants may be ineffective in CYP2D6 UMs.
- Anticancer medications—for example, tamoxifen is activated by CYP2D6, and IMs or PMs may have reduced benefit from tamoxifen therapy.
- Pain management—for example, codeine and tramadol are pro-drugs that require activation by CYP2D6 to achieve the desired analgesic effect. Oxycodone is also metabolized by CYP2D6, but there are no actionable prescribing recommendations for this gene-drug pair.
- Antimalarial medications—for example, primaquine must be metabolized by CYP2D6 to form the hydroxylated active metabolite that targets the parasite.
- Various therapies for genetic disorders—for example eliglustat used in the treatment of Gaucher disease; deutetrabenazine and valbenazine used in the treatment of Huntington disease and tardive dyskinesia—have reduced dose recommendations for CYP2D6 PMs. The CYP2D6 UMs may not achieve adequate concentrations of eliglustat and therefore CYP2D6 genotyping is required before initiation of eliglustat therapy.

It is important to note that CYP2D6 is the most common biomarker in drug responses for FDA drug labels; the list provided here is by no means exhaustive. Additional information on gene-drug interactions for CYP2D6 are available from ClinPGx (https://www.clinpgx.org/gene/PA128), CPIC (https://cpicpgx.org/genes-drugs/) and the FDA (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling) (search for “CYP2D6”).

## Therapeutic Recommendations Based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

### 2024 Statement from the US Food and Drug Administration (FDA)

In vitro studies indicate that the formation of ODV is catalyzed by CYP2D6; this has been confirmed in a clinical study showing that patients with low CYP2D6 levels (poor metabolizers) had increased levels of venlafaxine and reduced levels of ODV compared to people with normal CYP2D6 levels (extensive metabolizers).

Concomitant use of venlafaxine hydrochloride extended-release capsules increases C_max_ and AUC of a CYP2D6 substrate, which may increase the risk of toxicity of the CYP2D6 substrate … Consider reduction in dose of concomitant CYP2D6 substrates.

Concomitant use of a CYP3A inhibitor increases the C_max_ and AUC of venlafaxine and O-desmethylvenlafaxine (ODV), which may increase the risk of toxicity of venlafaxine hydrochloride extended-release capsules… Consider reducing the dose of venlafaxine hydrochloride extended-release capsules.

Table of Pharmacogenetic Associations, Section 1:

Drug | Gene | Affected Subgroups | Description of Gene-Drug interaction
Venlafaxine | CYP2D6 | poor metabolizers | Alters systemic parent drug and metabolite concentrations. Consider dosage reductions.

Please review the complete therapeutic recommendations that are located here: (1, 2).

### 2024 Summary of recommendations from the Dutch Pharmacogenetics Working Group (DPWG) of the Royal Dutch Association for the Advancement of Pharmacy (KNMP)

For CYP2D6 poor metaboliser and CYP2D6 intermediate metaboliser, there are indications of an increased risk of side effects and a reduced chance of efficacy.

These gene variations reduce the conversion of venlafaxine to the active metabolite O-desmethylvenlafaxine, whilst an association between high O-desmethylvenlafaxine/venlafaxine ratios and response without side effects was found.

[underlined: CYP2D6 Poor Metaboliser]

It is not possible to offer adequately substantiated advice for dose reduction based on the literature.

- avoid venlafaxine

Antidepressants that are not metabolised by CYP2D6 - or to a lesser extent - include, for example, duloxetine, mirtazapine, (es)citalopram and sertraline.

- if it is not possible to avoid venlafaxine and side effects occur:

- reduce the dose

- monitor the effect and side effects or check the plasma concentrations of venlafaxine and O-desmethylvenlafaxine

It is not known whether it is possible to reduce the dose to such an extent that the side effects disappear, while the effectiveness is maintained. In general, it is assumed that the effectiveness is determined by the sum of the plasma concentrations of venlafaxine and O-desmethylvenlafaxine. However, the side effects do not appear to be related to this sum.

Furthermore, a reduced effectiveness of venlafaxine has been observed in depression patients with this gene variation.

[underlined: CYP2D6 Intermediate Metaboliser]

It is not possible to offer adequately substantiated advice for dose reduction based on the literature.

- avoid venlafaxine

Antidepressants that are not metabolised by CYP2D6 - or to a lesser extent - include, for example, duloxetine, mirtazapine, (es)citalopram and sertraline.

- if it is not possible to avoid venlafaxine and side effects occur:

- reduce the dose

- monitor the effect and side effects or check the plasma concentrations of venlafaxine and O-desmethylvenlafaxine

It is not known whether it is possible to reduce the dose to such an extent that the side effects disappear, while the effectiveness is maintained. In general, it is assumed that the effectiveness is determined by the sum of the plasma concentrations of venlafaxine and O-desmethylvenlafaxine. However, the side effects do not appear to be related to this sum.

[underlined: CYP2D6 Ultrarapid Metaboliser]

Therapy adjustment is not required for UM.

Please review the complete therapeutic recommendations that are located here: (3).

### 2023 Summary of recommendations from the Clinical Pharmacogenetics Implementation Consortium (CPIC)

[underlined: CYP2D6 Ultrarapid metabolizer]

Regarding venlafaxine, increased metabolism to the active metabolite (O-desmethylvenlafaxine) is seen in UMs; however, there is minimal evidence to suggest that this is clinically significant. .... Therefore, no dosing recommendations are provided for venlafaxine … for CYP2D6 UMs.

[underlined: CYP2D6 Poor metabolizer]

Consider a clinically appropriate alternative antidepressant not predominantly metabolized by CYP2D6 (Classification of recommendation: Optional).

[underlined: CYP2D6 Normal metabolizer]

Initiate therapy with recommended starting dose. (Classification of recommendation: Strong)

[underlined: CYP2D6 Intermediate metabolizer]

No recommendation.

Please review the complete therapeutic recommendations that are located here: (4).

## Nomenclature of Selected CYP2D6 Alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2D6*2^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*2^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*3^[1]^ | 2550delA | NM_000106.6:c.775del (https://www.ncbi.nlm.nih.gov/clinvar/variation/16894) | NP_000097.3:p.Arg259fs | rs35742686 (https://www.ncbi.nlm.nih.gov/snp/rs35742686)
CYP2D6*4^[1]^ | 1846G>A | NM_000106.6:c.506-1G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/16889/) | Variant occurs in a non-coding region (splice variant causes a frameshift) | rs3892097 (https://www.ncbi.nlm.nih.gov/snp/rs3892097)
CYP2D6*5^[1]^ | Gene deletion (https://www.ncbi.nlm.nih.gov/clinvar/variation/16890/)
CYP2D6*6^[1]^ | 1707 del T | NM_000106.6:c.454delT (https://www.ncbi.nlm.nih.gov/clinvar/variation/16891/) | NP_000097.3:p.Trp152Glyfs | rs5030655 (https://www.ncbi.nlm.nih.gov/snp/rs5030655)
CYP2D6*7^[2]^ | 2936A>C | NM_000106.6:c.971A>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385) | NP_000097.3:p.His324Pro | rs5030867 (https://www.ncbi.nlm.nih.gov/snp/rs5030867)
CYP2D6*8^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*8^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*8^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*9^[1]^ | 2616delAAG | NM_000106.6:c.841_843del (https://www.ncbi.nlm.nih.gov/clinvar/variation/617719) | NP_000097.3:p.Lys281del | rs5030656 (https://www.ncbi.nlm.nih.gov/snp/rs5030656)
CYP2D6*10^[1]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*10^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*17^[1]^ | 1022C>T | NM_000106.6:c.320C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39379/) | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D6*17^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*17^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840/)
CYP2D6*12^[2]^ | 124G>A | NM_000106.6:c.124G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39387/) | NP_000097.3:p.Gly42Arg | rs5030862 (https://www.ncbi.nlm.nih.gov/snp/rs5030862)
CYP2D6*12^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*12^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*14^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*14^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*14^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*15^[2]^ | 137_138insT | NM_000106.6:c.137dup (https://www.ncbi.nlm.nih.gov/clinvar/variation/678343) | NP_000097.3:p.Leu47fs | rs774671100 (https://www.ncbi.nlm.nih.gov/snp/rs774671100)
CYP2D6*21^[2]^ | 2580_2581insC | NM_000106.5:c.805dup | NP_000097.3:p.Arg269fs | rs72549352 (https://www.ncbi.nlm.nih.gov/snp/rs72549352)
CYP2D6*21^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*21^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*28 | 19G>A | NM_000106.6:c.19G>A | NP_000097.3:p.Val7Met | rs72549358 (https://www.ncbi.nlm.nih.gov/snp/rs72549358)
CYP2D6*28 | 1705C>G | NM_000106.6:c.451C>G | NP_000097.3:p.Gln151Glu | rs78482768 (https://www.ncbi.nlm.nih.gov/snp/rs78482768)
CYP2D6*28 | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*28 | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*29^[1]^ | 1660G>A + 1662G>C | NM_000106.6:c.406G>A + NM_000106.6:c.408G>C | NP_000097.3:p.Val136Met + NP_000097.3:p.Val136= | rs61736512 (https://www.ncbi.nlm.nih.gov/snp/rs61736512) + rs1058164 (https://www.ncbi.nlm.nih.gov/snp/rs1058164)
CYP2D6*29^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*29^[1]^ | 3184G>A | NM_000106.6:c.1012G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/598263/) | NP_000097.3:p.Val338Met | rs59421388 (https://www.ncbi.nlm.nih.gov/snp/rs59421388)
CYP2D6*29^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*31^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D6*31^[2]^ | 4043G>A | NM_000106.6:c.1319G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/183247/) | NP_000097.3:p.Arg440His | rs267608319 (https://www.ncbi.nlm.nih.gov/snp/rs267608319)
CYP2D6*31^[2]^ | 4181G>C | NM_000106.6:c.1457G>C | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*36^[3]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*36^[3]^ | 4129C>G | NM_000106.6:c.1405C>G | NP_000097.3:p.Pro469Ala | rs1135833 (https://www.ncbi.nlm.nih.gov/snp/rs1135833)
CYP2D6*36^[3]^ | 4132A>G | NM_000106.6:c.1408A>G | NP_000097.3:p.Thr470Ala | rs1135835 (https://www.ncbi.nlm.nih.gov/snp/rs1135835)
CYP2D6*36^[3]^ | 4156C>T+4157A>C | NM_000106.6:c.1432C>T+ NM_000106.6:c.1433A>C | NP_000097.3:p.His47Ser | rs28371735 (https://www.ncbi.nlm.nih.gov/snp/rs28371735)+ rs766507177 (https://www.ncbi.nlm.nih.gov/snp/rs766507177)
CYP2D6*36^[3]^ | 4159G>C | NM_000106.6:c.1435G>C | NP_00097.3:p.Gly479Arg | n/a
CYP2D6*36^[3]^ | 4165T>G | NM_000106.6:c.1441T>G | NP_00097.3:p.Phe481Val | n/a
CYP2D6*36^[3]^ | 4168G>A+4169C>G | NM_000106.6:c.1444G>A+ NM_000106.6:c.1445C>G | NP_000097.3:p.Ala482Ser | rs74478221 (https://www.ncbi.nlm.nih.gov/snp/rs74478221)+ rs75467367 (https://www.ncbi.nlm.nih.gov/snp/rs75467367)
CYP2D6*36^[3]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D4*40^[2]^ | 1022C>T | NM_000106.6:c.320C>T | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D4*40^[2]^ | 1864_1865insTTTCGCCCC[2] | NM_000106.6:c.514TTTCGCCCC[3] | NP_000097.3:p.172FRP[3] | rs72549356 (https://www.ncbi.nlm.nih.gov/snp/rs72549356)
CYP2D4*40^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D4*40^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*41^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*41^[1]^ | 2989G>A | NM_000106.6:c.985+39G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39381/) | Variant occurs in a non-coding region (impacts splicing). | rs28371725 (https://www.ncbi.nlm.nih.gov/snp/rs28371725)
CYP2D6*41^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*49^[2]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*49^[2]^ | 1612T>A | NM_00106.6:c.358T>A | NP_000097.3:p.Phe120Ile | rs1135822 (https://www.ncbi.nlm.nih.gov/snp/rs1135822)
CYP2D6*49^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*56^[2]^ | 3202C>T | NM_000106.6:c.1030C>T | NP_000097.3:p.Arg344Ter | rs72549347 (https://www.ncbi.nlm.nih.gov/snp/rs72549347)
CYP2D6*56^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*59^[2]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*59^[2]^ | 2940G>A | NM_000106.6:c.975G>A | NP_000097.3:p.Pro325= | rs79292917 (https://www.ncbi.nlm.nih.gov/snp/rs79292917)
CYP2D6*59^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)

^[1]^ AMP Tier 1 allele, (64)

^[2]^ AMP Tier 2 allele, (64)

^[3]^ CYP2D6*36 is a gene conversion with CYP2D7; variants provided here are from the Pharmacogene Variation Consortium.

Alleles described in this table are selected based on discussion in the text above. This is not intended to be an exhaustive description of known alleles.

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS) (71).

Nomenclature for Cytochrome P450 enzymes is available from the Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium (18).AMP - Association for Molecular Pathology

## Acknowledgments

Version 3.0, published December 18, 2025:

The author would like to thank Marga Nijenhuis, PhD, Royal Dutch Pharmacists Association (KNMP), The Hague, The Netherlands; Laura Ramsey, PhD, Section Chief, Individualized Therapeutics; Co-Program Director, Clinical Pharmacology, Toxicology, and Therapeutic Innovations Fellowship; Associate Professor of Pediatrics, University of Missouri-Kansas City School of Medicine, Kansas City, MO, USA; and Izabel Cristina Rodrigues da Silva, MS, PhD, Assistant Professor, Clinical Analysis Laboratory, University of Brasília, Brasília, Brazil for providing an expert review of this summary.

Version 2.0, published June 29, 2020:

The author would like to thank Chad Bousman, MPH, PhD, Assistant Professor, Departments of Medical Genetics, Psychiatry, and Physiology & Pharmacology, University of Calgary, Calgary (AB), Canada; Bernard Esquivel MD, PhD, President of the Latin American Association for Personalized Medicine, Mexico City, Mexico; Inge Holsappel, Pharmacist at the Royal Dutch Pharmacists Association (KNMP), the Hague, the Netherlands (for reviewing the information regarding the guidelines of the DPWG); and Mark W. Miller PhD, Clinical Research Psychologist, National Center for PTSD and Professor of Psychiatry, Boston University School of Medicine, Boston (MA), USA, for reviewing this summary.

Version 1.0, published July 27, 2015:

The author would like to thank Stuart Scott, Associate Professor of Genetics and Genomic Sciences, Icahn School of Medicine at Mount Sinai, New York (NY), USA; Bruce G. Pollock, Vice President of Research and Director of the Campbell Family Mental Health Research Institute, and Professor of Psychiatry & Pharmacology at the University of Toronto, Toronto (ON), Canada, for reviewing this summary.

## Version History

The first version (v1.0) of this summary was publish on July 27, 2015 and is available here.

The second version (v2.0) of this summary was published on June 29, 2020 and is available here.

The third version (v3.0) of this summary was published on December 18, 2025. This version includes new and updated guidance for genotype guided venlafaxine therapy from CPIC and DPWG. Guidelines for allele testing by AMP are also included in this update.

## References

1 VENLAFAXINE HYDROCHLORIDE capsule, extended release. Plainsboro, NJ, USA: Advagen Pharma Ltd.; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=48a75840-64e4-4d44-9a62-009373003105.
2 FDA, U. Table of Pharmacogenetic Associations. 2022 10/26/2022 [cited 2024; Available from: https://www.fda.gov/medical-devices/precision-medicine/table-pharmacogenetic-associations#section3.
3 Beunk, L., M. Nijenhuis, B. Soree, N.J. de Boer-Veger, et al., Dutch Pharmacogenetics Working Group (DPWG) guideline for the gene-drug interaction between CYP2D6, CYP2C19 and non-SSRI/non-TCA antidepressants. Eur J Hum Genet, 2024. 32(11): p. 1371-1377.38956296
4 Bousman, C.A., J.M. Stevenson, L.B. Ramsey, K. Sangkuhl, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for CYP2D6, CYP2C19, CYP2B6, SLC6A4, and HTR2A Genotypes and Serotonin Reuptake Inhibitor Antidepressants. Clin Pharmacol Ther, 2023. 114(1): p. 51-68.37032427
5 Miller, M.W., Leveraging genetics to enhance the efficacy of PTSD pharmacotherapies. Neurosci Lett, 2018.29689343
6 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Drug/Small Molecule: Venlafaxine [Cited 19 May 2017]. Available from http://www.pharmgkb.org/drug/PA451866.
7 Mannheimer, B., T. Haslemo, J.D. Lindh, E. Eliasson, and E. Molden, Risperidone and Venlafaxine Metabolic Ratios Strongly Predict a CYP2D6 Poor Metabolizing Genotype. Ther Drug Monit, 2016. 38(1): p. 127-34.26418700
8 Montané Jaime, L.K., J. Paul, A. Lalla, G. Legall, and A. Gaedigk, Impact of CYP2D6 on venlafaxine metabolism in Trinidadian patients with major depressive disorder. Pharmacogenomics, 2018. 19(3): p. 197-212.29327975
9 Sasaki, T., N. Yasui-Furukori, H. Komahashi-Sasaki, M. Shinozaki, et al., CYP2D6*10 polymorphism and the enantioselective O-desmethylation of S-(+)- and R-(-)-venlafaxine in Japanese psychiatric patients. Basic Clin Pharmacol Toxicol, 2021. 128(5): p. 677-685.33470005
10 Eap, C.B., E. Lessard, P. Baumann, M. Brawand-Amey, et al., Role of CYP2D6 in the stereoselective disposition of venlafaxine in humans. Pharmacogenetics, 2003. 13(1): p. 39-47.12544511
11 VENLAFAXINE HYDROCHLORIDE tablet. Parsippany, NJ, USA: Teva Pharmaceuticals USA Inc.; 2023. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=37aaa8ac-4e0c-4e04-98b5-19b0d90d857c.
12 VENLAFAXINE XR. Mississauga, Ontario, Canada: Mint Pharmaceuticals Inc.; 2024. Available from: https://health-products.canada.ca/dpd-bdpp/info?lang=eng&code=101206.
13 Tveit, K., M. Hermann, R.M. Nilsen, S.M. Wallerstedt, et al., Age of onset for increased dose-adjusted serum concentrations of antidepressants and association with sex and genotype: An observational study of 34,777 individuals. Eur J Clin Pharmacol, 2024. 80(3): p. 435-444.38197945
14 Alenezi, M. and R.K.S. Badhan, Precision dosing of venlafaxine during pregnancy: a pharmacokinetics modelling approach. J Pharm Pharmacol, 2024. 76(2): p. 122-137.38142123
15 Venlafaxine, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/30000251.
16 Pan, X. and K. Rowland Yeo, Advancing inclusive healthcare through PBPK modelling: predicting the impact of CYP genotypes and enzyme ontogenies on infant exposures of venlafaxine and its active metabolite O-desmethylvenlafaxine in lactation. J Pharmacokinet Pharmacodyn, 2025. 52(2): p. 22.40185984
17 Nofziger, C., A.J. Turner, K. Sangkuhl, M. Whirl-Carrillo, et al., PharmVar GeneFocus: CYP2D6. Clin Pharmacol Ther, 2020. 107(1): p. 154-170.31544239
18 Gaedigk, A., M. Ingelman-Sundberg, N.A. Miller, J.S. Leeder, et al., The Pharmacogene Variation (PharmVar) Consortium: Incorporation of the Human Cytochrome P450 (CYP) Allele Nomenclature Database. Clin Pharmacol Ther, 2018. 103(3): p. 399-401.29134625
19 Caudle, K.E., H.M. Dunnenberger, R.R. Freimuth, J.F. Peterson, et al., Standardizing terms for clinical pharmacogenetic test results: consensus terms from the Clinical Pharmacogenetics Implementation Consortium (CPIC). Genet Med, 2017. 19(2): p. 215-223.27441996
20 CYP26 Allele Functionality Reference [Cited Nov 19, 2025]. Available from https://files.cpicpgx.org/data/report/current/allele_function_reference/CYP2D6_allele_functionality_reference.xlsx.
21 Yokota, H., S. Tamura, H. Furuya, S. Kimura, et al., Evidence for a new variant CYP2D6 allele CYP2D6J in a Japanese population associated with lower in vivo rates of sparteine metabolism. Pharmacogenetics, 1993. 3(5): p. 256-63.8287064
22 Ingelman-Sundberg, M., Genetic polymorphisms of cytochrome P450 2D6 (CYP2D6): clinical consequences, evolutionary aspects and functional diversity. Pharmacogenomics J, 2005. 5(1): p. 6-13.15492763
23 PharmGKB [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*10 [Cited 26 Sept 2016]. Available from https://www.pharmgkb.org/haplotype/PA165816582.
24 Bradford, L.D., CYP2D6 allele frequency in European Caucasians, Asians, Africans and their descendants. Pharmacogenomics, 2002. 3(2): p. 229-43.11972444
25 PharmVar. CYP2D6. 2024 [cited 2024; Available from: https://www.pharmvar.org/gene/CYP2D6.
26 Koopmans, A.B., M.H. Braakman, D.J. Vinkers, H.W. Hoek, and P.N. van Harten, Meta-analysis of probability estimates of worldwide variation of CYP2D6 and CYP2C19. Transl Psychiatry, 2021. 11(1): p. 141.33627619
27 A, P.S., P. Dorado, A. Borbon, F. de Andres, et al., High prevalence of CYP2D6 ultrarapid metabolizers in a mestizo Colombian population in relation to Hispanic mestizo populations. Pharmacogenomics, 2020. 21(17): p. 1227-1236.
28 Ingelman-Sundberg, M., Pharmacogenetics: an opportunity for a safer and more efficient pharmacotherapy. J Intern Med, 2001. 250(3): p. 186-200.11555122
29 Aklillu, E., K. Herrlin, L.L. Gustafsson, L. Bertilsson, and M. Ingelman-Sundberg, Evidence for environmental influence on CYP2D6-catalysed debrisoquine hydroxylation as demonstrated by phenotyping and genotyping of Ethiopians living in Ethiopia or in Sweden. Pharmacogenetics, 2002. 12(5): p. 375-83.12142727
30 Cicali, E.J., D.M. Smith, B.Q. Duong, L.G. Kovar, et al., A Scoping Review of the Evidence Behind Cytochrome P450 2D6 Isoenzyme Inhibitor Classifications. Clin Pharmacol Ther, 2020. 108(1): p. 116-125.31910286
31 Smith, D.M., K.W. Weitzel, A.R. Elsey, T. Langaee, et al., CYP2D6-guided opioid therapy improves pain control in CYP2D6 intermediate and poor metabolizers: a pragmatic clinical trial. Genet Med, 2019. 21(8): p. 1842-1850.30670877
32 Monte, A.A., K. West, K.T. McDaniel, H.K. Flaten, et al., CYP2D6 Genotype Phenotype Discordance Due to Drug-Drug Interaction. Clin Pharmacol Ther, 2018. 104(5): p. 933-939.29882961
33 Patel, J.N., S.A. Morris, R. Torres, B. Rhead, et al., Pharmacogenomic insights in psychiatric care: uncovering novel actionability, allele-specific CYP2D6 copy number variation, and phenoconversion in 15,000 patients. Mol Psychiatry, 2024. 29(11): p. 3495-3502.38783055
34 den Uil, M.G., H.W. Hut, K.R. Wagelaar, H. Abdullah-Koolmees, et al., Pharmacogenetics and phenoconversion: the influence on side effects experienced by psychiatric patients. Front Genet, 2023. 14: p. 1249164.37693320
35 Cicali, E.J., A.L. Elchynski, K.J. Cook, J.T. Houder, et al., How to Integrate CYP2D6 Phenoconversion Into Clinical Pharmacogenetics: A Tutorial. Clin Pharmacol Ther, 2021. 110(3): p. 677-687.34231197
36 Ozbey, G., F.C. Celikel, B.E. Cumurcu, D. Kan, et al., Influence of ABCB1 polymorphisms and serum concentrations on venlafaxine response in patients with major depressive disorder. Nord J Psychiatry, 2017. 71(3): p. 230-237.28079463
37 Scherf-Clavel, M., H. Weber, C. Wurst, S. Stonawski, et al., Effects of Pharmacokinetic Gene Variation on Therapeutic Drug Levels and Antidepressant Treatment Response. Pharmacopsychiatry, 2022. 55(5): p. 246-254.35839823
38 Sangkuhl, K., J.C. Stingl, M. Turpeinen, R.B. Altman, and T.E. Klein, PharmGKB summary: venlafaxine pathway. Pharmacogenet Genomics, 2014. 24(1): p. 62-72.24128936
39 Ahmed, A.T., J.M. Biernacka, G. Jenkins, A.J. Rush, et al., Pharmacokinetic-Pharmacodynamic interaction associated with venlafaxine-XR remission in patients with major depressive disorder with history of citalopram / escitalopram treatment failure. J Affect Disord, 2019. 246: p. 62-68.30578947
40 Komahashi-Sasaki, H., N. Yasui-Furukori, T. Sasaki, M. Shinozaki, et al., Effects of CYP2D6 Genotypes on Venlafaxine Metabolism in Japanese Psychiatric Patients With Depression. Ther Drug Monit, 2021. 43(5): p. 681-687.33306568
41 Berm, E., R. Kok, E. Hak, and B. Wilffert, Relation between CYP2D6 Genotype, Phenotype and Therapeutic Drug Concentrations among Nortriptyline and Venlafaxine Users in Old Age Psychiatry. Pharmacopsychiatry, 2016. 49(5): p. 186-190.27101231
42 Berm, E.J., E. Hak, M. Postma, M. Boshuisen, et al., Effects and cost-effectiveness of pharmacogenetic screening for CYP2D6 among older adults starting therapy with nortriptyline or venlafaxine: study protocol for a pragmatic randomized controlled trial (CYSCEtrial). Trials, 2015. 16: p. 37.25636328
43 Waade, R.B., M. Hermann, H.L. Moe, and E. Molden, Impact of age on serum concentrations of venlafaxine and escitalopram in different CYP2D6 and CYP2C19 genotype subgroups. Eur J Clin Pharmacol, 2014. 70(8): p. 933-40.24858822
44 van der Lee, M., H.J. Guchelaar, and J.J. Swen, Substrate specificity of CYP2D6 genetic variants. Pharmacogenomics, 2021. 22(16): p. 1081-1089.34569808
45 Shams, M.E., B. Arneth, C. Hiemke, A. Dragicevic, et al., CYP2D6 polymorphism and clinical effect of the antidepressant venlafaxine. Journal of clinical pharmacy and therapeutics, 2006. 31(5): p. 493-502.16958828
46 Johnson, E.M., E. Whyte, B.H. Mulsant, B.G. Pollock, et al., Cardiovascular changes associated with venlafaxine in the treatment of late-life depression. Am J Geriatr Psychiatry, 2006. 14(9): p. 796-802.16943176
47 Austin-Zimmerman, I., M. Wronska, B. Wang, H. Irizar, et al., The Influence of CYP2D6 and CYP2C19 Genetic Variation on Diabetes Mellitus Risk in People Taking Antidepressants and Antipsychotics. Genes (Basel), 2021. 12(11).34828364
48 Olson, M.C., A. Maciel, J.F. Gariepy, A. Cullors, et al., Clinical Impact of Pharmacogenetic-Guided Treatment for Patients Exhibiting Neuropsychiatric Disorders: A Randomized Controlled Trial. Prim Care Companion CNS Disord, 2017. 19(2).28314093
49 Garcia, S., M. Schuh, A. Cheema, H. Atwal, and P.S. Atwal, Palpitations and Asthenia Associated with Venlafaxine in a CYP2D6 Poor Metabolizer and CYP2C19 Intermediate Metabolizer. Case Rep Genet, 2017. 2017: p. 6236714.29123929
50 Lloret-Linares, C., Y. Daali, S. Chevret, I. Nieto, et al., Exploring venlafaxine pharmacokinetic variability with a phenotyping approach, a multicentric french-swiss study (MARVEL study). BMC Pharmacol Toxicol, 2017. 18(1): p. 70.29115994
51 Burke, W. and K. Thummel, A call for accurate pharmacogenetic labeling: telling it like it is. JAMA Intern Med, 2014. 174(12): p. 1945-6.25317574
52 Watanabe, Y., Y. Asami, Y. Hirano, K. Kuribayashi, et al., Factors impacting the efficacy of venlafaxine extended release 75-225 mg/day in patients with major depressive disorder: exploratory post hoc subgroup analyses of a randomized, double-blind, placebo-controlled study in Japan. Neuropsychiatr Dis Treat, 2018. 14: p. 1261-1272.29844674
53 Taranu, A., R. Colle, F. Gressier, K. El Asmar, et al., Should a routine genotyping of CYP2D6 and CYP2C19 genetic polymorphisms be recommended to predict venlafaxine efficacy in depressed patients treated in psychiatric settings? Pharmacogenomics, 2017.28480819
54 Yesavage, J.A., J.O. Brooks, 3rd, J. Taylor, and J. Tinklenberg, Development of aphasia, apraxia, and agnosia and decline in Alzheimer's disease. Am J Psychiatry, 1993. 150(5): p. 742-7.8480819
55 van der Schans, J., E. Hak, M. Postma, L. Breuning, et al., Effects of Pharmacogenetic Screening for CYP2D6 Among Elderly Starting Therapy With Nortriptyline or Venlafaxine: A Pragmatic Randomized Controlled Trial (CYSCE Trial). J Clin Psychopharmacol, 2019. 39(6): p. 583-590.31688392
56 Men, X., Z.L. Taylor, V.S. Marshe, D.M. Blumberger, et al., CYP2D6 Phenotype Influences Pharmacokinetic Parameters of Venlafaxine: Results from a Population Pharmacokinetic Model in Older Adults with Depression. Clin Pharmacol Ther, 2024. 115(5): p. 1065-1074.38284409
57 Hole, K., M. Arnestad, E. Molden, and T. Haslemo, Dose-Dependent Inhibition of CYP2D6 by Bupropion in Patients With Depression. J Clin Psychopharmacol, 2021. 41(3): p. 281-285.33905640
58 Luecht, U.R., W. Scholz, A.K. Geiben, E. Haen, and G. Hempel, Physiologically Based Pharmacokinetic Model of CYP2D6 Associated Interaction Between Venlafaxine and Strong Inhibitor Bupropion-The Influence of Age-Relevant Changes and Inhibitory Dose to Classify Therapeutical Success and Harm. Pharmaceutics, 2025. 17(2).40006546
59 Aly, S.M., B. Hennart, J.M. Gaulier, and D. Allorge, Effect of CYP2D6, 2C19, and 3A4 Phenoconversion in Drug-Related Deaths. Toxics, 2024. 12(4).38668482
60 Yan, D., M. Wu, W. Hu, Y. Li, et al., Effects of Zuojin Pill (Rhizoma Coptidis and Fructus Evodiae preparation) on the pharmacokinetics and side effects of venlafaxine in humans. Basic Clin Pharmacol Toxicol, 2022. 130(4): p. 522-530.35132786
61 Brogdon, H.D., M.M. McPhee, M.F. Paine, E.J. Cox, and A.G. Burns, A Case of Potential Pharmacokinetic Kratom-drug Interactions Resulting in Toxicity and Subsequent Treatment of Kratom Use Disorder With Buprenorphine/Naloxone. J Addict Med, 2022. 16(5): p. 606-609.35165231
62 Cho, C.K., P. Kang, C.G. Jang, S.Y. Lee, et al., PBPK modeling to predict the pharmacokinetics of venlafaxine and its active metabolite in different CYP2D6 genotypes and drug-drug interactions with clarithromycin and paroxetine. Arch Pharm Res, 2024. 47(5): p. 481-504.38664354
63 Shen, C., H. Yang, W. Shao, L. Zheng, et al., Physiologically Based Pharmacokinetic Modeling to Unravel the Drug-gene Interactions of Venlafaxine: Based on Activity Score-dependent Metabolism by CYP2D6 and CYP2C19 Polymorphisms. Pharm Res, 2024. 41(4): p. 731-749.38443631
64 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and the European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021. 23(9): p. 1047-1064.34118403
65 Hicks, J.K., J.R. Bishop, K. Sangkuhl, D.J. Muller, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for CYP2D6 and CYP2C19 Genotypes and Dosing of Selective Serotonin Reuptake Inhibitors. Clin Pharmacol Ther, 2015. 98(2): p. 127-34.25974703
66 Jarvis, J.P., A.P. Peter, and J.A. Shaman, Consequences of CYP2D6 Copy-Number Variation for Pharmacogenomics in Psychiatry. Front Psychiatry, 2019. 10: p. 432.31281270
67 O'Shea, J., M. Ledwidge, J. Gallagher, C. Keenan, and C. Ryan, Pharmacogenetic interventions to improve outcomes in patients with multimorbidity or prescribed polypharmacy: a systematic review. Pharmacogenomics J, 2022. 22(2): p. 89-99.35194175
68 Hayashi, M., D.A. Hamdy, and S.H. Mahmoud, Applications for pharmacogenomics in pharmacy practice: A scoping review. Res Social Adm Pharm, 2022. 18(7): p. 3094-3118.34474980
69 Swen, J.J., C.H. van der Wouden, L.E. Manson, H. Abdullah-Koolmees, et al., A 12-gene pharmacogenetic panel to prevent adverse drug reactions: an open-label, multicentre, controlled, cluster-randomised crossover implementation study. Lancet, 2023. 401(10374): p. 347-356.36739136
70 Hjemas, B.J., K. Bovre, K. Bjerknes, L. Mathiesen, et al., Implementation of pharmacogenetic testing in medication reviews in a hospital setting. Br J Clin Pharmacol, 2023. 89(10): p. 3116-3125.37277227
71 den Dunnen, J.T., R. Dalgleish, D.R. Maglott, R.K. Hart, et al., HGVS Recommendations for the Description of Sequence Variants: 2016 Update. Hum Mutat, 2016. 37(6): p. 564-9.26931183

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug. Certain terms, genes and genetic variants may be corrected in accordance to nomenclature standards, where necessary. We have given the full name of abbreviations where necessary, other author insertions are shown in square brackets.

## Related Summaries by Gene

Amitriptyline Therapy and CYP2D6 and CYP2C19 Genotype

Aripiprazole Therapy and CYP2D6 Genotype

Atomoxetine Therapy and CYP2D6 Genotype

CYP2D6 Overview: Allele and Phenotype Frequencies

Carvedilol Therapy and CYP2D6 Genotype

Clozapine Therapy and CYP Genotype

Codeine Therapy and CYP2D6 Genotype

Deutetrabenazine Therapy and CYP2D6 Genotype

Eliglustat Therapy and CYP2D6 Genotype

Imipramine Therapy and CYP2D6 and CYP2C19 Genotype

Metoprolol Therapy and CYP2D6 Genotype

Oxycodone Therapy and CYP2D6 Genotype

Primaquine Therapy and G6PD and CYP2D6 Genotype

Propafenone Therapy and CYP2D6 Genotype

Risperidone Therapy and CYP2D6 Genotype

Tamoxifen Therapy and CYP2D6 Genotype

Thioridazine Therapy and CYP2D6 Genotypes

Tramadol Therapy and CYP2D6 Genotype

Valbenazine Therapy and CYP2D6 Genotype

## Tests in GTR by Condition

Venlafaxine response (https://www.ncbi.nlm.nih.gov/gtr/tests/?condition=CN078028&term=CN078028[DISCUI]&display_string=Venlafaxine response)

## Tests in GTR by Gene

CYP2D6 gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=1565[geneid]+AND+CN078028[cui])