# Vemurafenib Therapy and BRAF and NRAS Genotype

## Introduction

Vemurafenib is a kinase inhibitor used in the treatment of individuals with unresectable or metastatic melanoma with the BRAF V600E variant or Erdheim-Chester disease with a BRAF V600 variation.

The BRAF protein is an intracellular kinase in the mitogen-activated protein kinase (MAPK) pathway. Signaling via BRAF is involved in regulating important cell functions such as cell growth, division, differentiation, and apoptosis. The BRAF gene is also a proto-oncogene—when mutated it can transform normal cells into cancerous cells.

Variation in the kinase domain of BRAF have been associated with various cancers. The most common BRAF variant, V600E, constitutively activates the kinase, and causes cell proliferation in the absence of growth factors that would normally be required. The V600E variant is detected in approximately 50% of melanomas (1, 2).

The FDA-approved drug label for vemurafenib states that the presence of BRAF V600E mutation in tumor specimens should be confirmed, using an FDA-approved test, before starting treatment with vemurafenib. The label also states that vemurafenib is not indicated for treatment of individuals with wild-type BRAF melanoma (3).

Variations in NRAS, also a proto-oncogene, are found in up to 30% of all malignancies and in approximately 15-20% of melanomas. Variants in NRAS that activate MAPK signaling have been implicated in acquired resistance to BRAF inhibitors. Vemurafenib’s label warns that one adverse effect associated with therapy may be the progression of pre-existing chronic myelomonocytic leukemia with NRAS mutation (3). Other adverse effects include arthralgia, rash, alopecia, photosensitivity reaction, pruritus, and skin papilloma. Concomitant use of vemurafenib with medications that inhibit or induce the cytochrome P450 protein CYP3A4 can alter an individual’s exposure to vemurafenib and increase the risk of toxicity or decrease efficacy (3).

## Drug: Vemurafenib

Vemurafenib is a BRAF kinase inhibitor indicated for the treatment of individuals with unresectable or metastatic melanoma with the BRAF V600E variant, as detected by an FDA-approved test. It is also approved for the treatment of Erdheim-Chester disease with V600 variant BRAF. Vemurafenib was one of the first molecularly targeted agents to receive FDA (US Food and Drug Administration) approval for advanced melanoma (3). Off-label uses of vemurafenib include the treatment of other BRAF V600E positive tumors that are not responding to traditional treatments such as refractory hairy cell leukemia and other BRAF V600 mutant cancers (4, 5). The recommended dose of vemurafenib is 960 mg orally every 12 hours; however, when concomitant use with a strong CYP3A4 inducer is unavoidable, an additional 240 mg vemurafenib may be administered—if tolerated (3). Strong inducers of CYP3A4 such as rifampin decreased the total plasma exposure of vemurafenib by 40%, relative to vemurafenib alone (3).

Skin cancer is the most common of all cancers. Although melanoma is the least common type of skin cancer, accounting for approximately 1% of cases, it is responsible for most deaths from skin cancer. In the US, the lifetime risk of melanoma is approximately 2.5% for whites, 0.5% for Hispanics, and 0.1% for blacks (6). Most cases of malignant melanoma are diagnosed at an early stage, when the tumor is localized and surgical excision can be curative. However, the 5-year survival rate drops from 98% for localized disease, to only 16% for individuals with metastatic disease.

For individuals with advanced metastatic or unresectable malignant melanoma, treatment options typically include immunotherapy and targeted therapy. Although chemotherapy was once widely used, it does not increase survival and therefore its use is now limited to individuals who are not candidates for further treatment with either immunotherapy or targeted therapy, and for whom there is no appropriate clinical trial. High dose interleukin2 (IL2) therapy may be successful in a minority of cases but can only be used in select individuals with good organ function because of the risk of severe toxicity. Immunotherapy drugs include antibodies that target programmed cell death protein 1 (PD1), such as nivolumab and pembrolizumab (7), and ipilimumab, a monoclonal antibody that targets cytotoxic T-lymphocyte-associated protein 4 (CTLA4) (8). Oncolytic virus therapy, CD3 bispecifics, tumor-infiltrating lymphocyte therapy, and TCR engineered T-cell therapy are some of the newer therapeutic approaches for melanoma (9).

Targeted therapies are designed to inhibit components of the MAPK signaling pathway, primarily when it is constitutively activated in melanomas with the activating BRAF mutation, V600E. Drugs in this category include vemurafenib, encorafenib and dabrafenib, which inhibit BRAF, and trametinib, binimetinib and cobimetinib, which target downstream kinases MEK1 and MEK2.

Vemurafenib is a potent inhibitor of the kinase domain of V600 mutated BRAF. It acts by decreasing signaling through the MAPK pathway, leading to the reduced transcription of genes involved in various cellular responses. Approximately 50% of cases of metastatic melanoma are found to have the BRAF V600E activating variant (1, 2). The FDA drug label warns that BRAF inhibitors have been shown to increase cell proliferation in BRAF wild-type cells in vitro and thus only individuals with V600E mutations should be treated with vemurafenib (3). Previously, it was thought that other BRAF V600 variants such as V600K would not benefit from vemurafenib therapy, but there have been reports of successful treatment of individuals with this mutation (10). Likewise, other cancers with BRAF V600 mutation have also been treated off-label with vemurafenib (5).

Combining vemurafenib with MEK inhibitors may potentiate its effects, reduce the risk of secondary skin cancers, and has been shown to extend survival. As a result, vemurafenib is rarely given as a monotherapy (11, 12, 13). The National Comprehensive Cancer Network (NCCN) Guidelines recommend vemurafenib/cobimetinib combination therapy in BRAF V600 mutation-positive metastatic melanoma (13). Vemurafenib has also been studied as an adjuvant therapy to manage high-risk resected melanoma (14). However, it is not yet approved by the FDA for this indication and is thus not recommend by the NCCN guideline panel for cutaneous melanoma (13). There is evidence that combining BRAF inhibitors, like vemurafenib, with radiation therapy may lead to higher rates of acute or late toxicity and thus may not be advisable (15).

Both targeted therapy with vemurafenib and immunotherapy regimens (namely, nivolumab plus ipilimumab) have been shown to improve overall survival in individuals with metastatic melanoma compared with chemotherapy (16, 17). However, nearly every individual treated with a BRAF inhibitor eventually demonstrated disease progression (18). Most individuals developed mechanisms of acquired resistance, which is sometimes associated with NRAS variants, and approximately 15% of individuals did not achieve tumor regression at all (19, 20, 21, 22, 23, 24). A meta-analysis reviewed results from 18 clinical trials and reported that PD-(L)1/BRAF/MEK inhibitor triple therapy was superior to ipilimumab/nivolumab in terms of progression free survival and overall response rate, with ipilimumab/nivolumab showing a higher risk of grade 3 or higher treatment related adverse events (25). Other clinical trials that examined the sequence of therapies for metastatic melanoma (DREAMseq and SECOMBIT) demonstrated an overall superiority of combination immunotherapy (nivolumab and ipilimumab) as first line treatment followed by targeted therapy versus BRAF/MEK inhibitor targeted therapy (either dabrafenib and trametinib or encorafenib and binimetinib) followed by immunotherapy (26, 27, 28).

The most common adverse events associated with vemurafenib are skin lesions (benign and malignant), fever, arthralgia, and fatigue. Skin lesions, such as cutaneous squamous cell carcinoma, tend to occur during the first 8 weeks of treatment. Regular evaluation of the skin is recommended, with excision of suspicious lesions (29). Other severe cutaneous reactions such as drug reaction with eosinophilia and systemic symptoms (DRESS) or toxic epidermal necrolysis require immediate discontinuation of vemurafenib (3, 30). Liver enzymes (transaminases, alkaline phosphatase, and bilirubin) should also be monitored because of the risk of liver injury. Cardiotoxicity has also been reported, though most cases were reversible with dose reduction, treatment pause or therapeutic interventions (31). Combining BRAF- and MEK-inhibitors helps reduce the odds of dermatologic side effects, but not gastrointestinal side effects such as mesenteric panniculitis, diarrhea, vomiting and nausea (32, 33). Administration of vemurafenib with a strong CYP3A4 inhibitor can increase vemurafenib concentration and may lead to toxicity; a dose reduction of vemurafenib may be necessary (3).

Erdheim-Chester disease is a rare non-Langerhans cell histiocytosis, first described in 1930 as a lipoid granulomatosis. It is characterized by infiltration of tissues by histiocytes with a foamy appearance and fibrotic encapsulation. (34, 35) There are approximately 1,500 known cases of the disorder since its first description, and it is estimated that 50-70% of cases can be attributed to BRAF V600E activating mutations. Most of the remaining cases harbor pathogenic variants leading to constitutive activation of other MAPK components such as MAP2K1 (35). Symptoms can affect the cardiac, skeletal, neurologic, renal, or multiple systems and vary widely in their severity between known cases. The FDA-approved dose of vemurafenib is 960 mg every 12 hours for Erdheim-Chester disease (3). Adverse reactions requiring medication discontinuation can occur (3, 36), therapy can then be resumed at a lower dose. Indeed, a lower dose of the medication may be sufficient to control EDC, as has been reported in at least one individual (37). Additional strategies such as co-medication with an IL-1 receptor antagonist may also improve medication adherence rates by reducing adverse reactions (36).

## Gene: BRAF

The rapidly accelerated fibrosarcoma (RAF) proteins are a family of intracellular kinases within the MAPK signaling pathway. The RAF family has 3 members, ARAF, BRAF, and CRAF (38). The RAF locus, along with RAS (see below), are proto-oncogenes.

Proto-oncogenes are genes that, when mutated or expressed at abnormally high levels, can transform normal cells into cancerous cells. Proto-oncogenes typically encode proteins that stimulate cell division, inhibit cell differentiation, and halt cell death. The increased production of oncogenic proteins can lead to the proliferation of poorly differentiated cancer cells (39).

Germline pathogenic variants in BRAF, as well as other components of the MAPK signaling pathway, are associated with birth defects, such as cardiofaciocutaneous syndrome, which is characterized by heart defects, intellectual disability, and a distinctive facial dysmorphology. Somatic BRAF mutations are also associated with several malignancies, including lung adenocarcinoma, mucinous adenoma, ductal carcinoma of the pancreas, colorectal carcinoma, and malignant melanoma. Variants in BRAF are also associated with Erdheim-Chester disease (40) and a form of LEOPARD syndrome (type 3) (41, 42).

Variations in BRAF are detectable in approximately 50—60% of malignant melanomas, and drive progression of the disease (1, 2, 8). The BRAF variant V600E (NM_004333.4:c.1799T>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/13961/); NP_004324.2:p.Val600Glu (https://www.ncbi.nlm.nih.gov/clinvar/variation/13961/)) accounts for approximately 90% of variants. The variant BRAF protein kinase is constitutively active and a highly potent oncogene, with an increase in kinase activity by as much as 500-fold compared to the wild-type (43). The second most common BRAF variant is V600K (valine substituted with lysine). Substitutions at other sites are rarer (44, 45).

Several drugs have been developed to target BRAF mutations, and so far, a few drugs have been FDA- approved including encorafenib, vemurafenib, and dabrafenib. Unfortunately, less progress has been made in developing targeted therapies for melanoma with wild-type BRAF. There are fewer treatment options available, but these include immunotherapy and MEK inhibitors (7, 46).

## Gene: NRAS

The RAS family contains 3 genes, HRAS, NRAS, and KRAS, which are essential components of several signaling pathways. They act as signal transducers, coupling cell surface receptors to intracellular signaling pathways.

The RAS proteins have intrinsic GTPase activity, they are activated by a guanine nucleotide-exchange factor and inactivated by a GTPase activating protein. The RAS proteins regulate cell signal transduction by acting as a switch; they cycle between "on" (GTP-bound) or "off" (GDP-bound) conformations. In the "on" position, RAS proteins transmit extracellular growth signals to the nucleus, primarily via the MAPK pathway. Cells are subsequently stimulated to grow, divide, mature, and differentiate.

Variations in RAS genes lead to RAS proteins that are resistant to GTPase, so that GTP-remains permanently bound and the receptor remains "on," providing a continual growth stimulus to cells. Such activating RAS variants are common, having been detected in colorectal cancer, lung cancer, pancreatic cancer, and melanoma.

Variations in NRAS are detectable in 15–30% of melanomas, clustering at codons 12, 13, and 61 (47, 48). These NRAS variants are the second most common oncogenic “driver” mutation in malignant melanomas, behind alterations in BRAF (49).Variants in NRAS are associated with more aggressive melanomas, and generally a poorer prognosis (49). At the time of writing, no therapies that specifically target NRAS have been approved. The NRAS protein, like other RAS family members, does not have a protein conformation with bona fide druggable pockets which complicates drug development. Even if the protein is effectively targeted, it has many downstream effectors other than the oncogenic MEK-ERK and PI3K-Akt pathways that may lead to undesirable side effects (50). Approaches to change NRAS interaction with the plasma membrane or target the nucleotide binding site have not been successful thus far, but other therapies are being trialed (51).

Genetic variants in NRAS are also associated with several other conditions, including Noonan syndrome (type 6), somatic rectal cancer, follicular thyroid cancer, autoimmune lymphoproliferative syndrome, and juvenile myelomonocytic leukemia.

### Other genes of interest: The cytochrome P450 (CYP450) family and CYP3A4

The CYP450 superfamily is a large and diverse group of enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs. The genes that encode CYP450 proteins are highly polymorphic and can result in reduced, absent, or increased enzyme activity. Although around 40 variant CYP3A4 alleles have been reported, most have not been shown to alter the activity of CYP3A4 (52, 53). To date, only 3 loss-of-function CYP3A4 alleles have been identified (CYP3A4*6, CYP3A4*20 and CYP3A4*26) (54, 55).

The CYP3A4*22 allele has decreased function and explains 12% of the variation in CYP3A4 activity (56). This variant that is present in 3.2–10.6% of the Dutch population and 5.2–8.3% of the population in America (57). The Allele Frequency Aggregator project reports this reduced-function allele to be present in just under 5% of the global population, with the lowest prevalence in Asian and African populations (58). The 1000 Genomes Project phase 3 data release estimates global prevalence to be slightly lower (~1%); a minor allele frequency of 5% is reported for the European average (59).

The CYP3A4*20 allele contains a premature stop codon that results in a loss-of-function of CYP3A4. It appears to be the most common CYP3A4 loss-of-function allele but is still relatively rare, with approximately 0.2% of European Americans and 0.05% African Americans who are heterozygous. However, in Spain, the CYP3A4*20 allele is present in 1.2% of the population, and up to 3.8% in specific Spanish regions (54).

Other factors can affect CYP enzyme activity in addition to genetic variation, including concomitant medications. Medications that are CYP inhibitors or inducers can change the relative drug exposure of an individual taking a CYP substrate. According to the FDA approved drug label, in vitro studies indicate that vemurafenib is a substrate for CYP3A4 and an inhibitor of CYP1A2, CYP2A6, CYP2B6, CYP2C8, CYP2C9, CYP2C19, CYP2D6, and CYP3A4/5 (3). However, there are no vemurafenib dosing recommendations based on CYP3A4 genotype.

## Linking BRAF and NRAS Genetic Variation with Treatment Response

Vemurafenib should only be used when there is a molecularly confirmed V600 variant in BRAF (3). Though initially recommended only for V600E variants, there is evidence that melanoma with V600K BRAF is also inhibited by vemurafenib therapy (10, 20, 60).

There is evidence that other malignancies (such as chronic myelomonocytic leukemia) with NRAS mutation may progress during vemurafenib treatment (3). Additionally, secondary mutations in NRAS can also occur in BRAF V600 mutant tumors leading to vemurafenib resistance (22, 61). Clinical practice guidelines from groups such as the National Comprehensive Cancer Network, the American Society of Clinical Oncology, or American Academy of Dermatology should be consulted for best practices to manage these cases (13, 62, 63).

In cases of melanoma where NRAS mutation occurs independent of BRAF mutations, the treatment options are less straightforward. In one study, MEK inhibitors were used as a second line treatment after failing immunotherapy leading to a median overall survival of 7.1 months (64). Studies using in vitro melanoma models indicate that some cancers may be more susceptible to this therapeutic approach. In “sensitive” cell lines, the use of MEK and BRAF inhibitors had enhanced antiproliferation effects downstream of a mutated, constitutively active NRAS protein; however not all melanoma types are sensitive to MEK and BRAF inhibition (65).

## Genetic Testing

The NIH Genetic Testing Registry, GTR, includes genetic tests that are available for the genes BRAF (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=673%5Bgeneid%5D) and NRAS (http://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=4893%5Bgeneid%5D), as well as tests for Erdheim-Chester disease (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=Erdheim-Chester). Additionally, there are FDA-approved companion diagnostics for BRAF gene sequencing (66).

The FDA-approved label for vemurafenib states that the presence of the BRAF V600E mutation should be confirmed in tumor specimens using an FDA-approved test before starting treatment with vemurafenib. The label states that vemurafenib is not indicated for treatment of individuals with wild-type BRAF melanoma. Additionally, vemurafenib is only indicated for treatment of Erdheim-Chester disease in individuals with V600 mutated BRAF. (3)

## Therapeutic Recommendations Based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

2024 Statement from the US Food and Drug Administration (FDA):

Vemurafenib is indicated for the treatment of patients with unresectable or metastatic melanoma with BRAF V600E mutation as detected by an FDA-approved test.

Limitation of Use: vemurafenib is not indicated for treatment of patients with wild-type BRAF melanoma.

Vemurafenib is indicated for the treatment of patients with Erdheim-Chester Disease (ECD) with BRAF V600 mutation.

Patient Selection for treatment of melanoma: Confirm the presence of BRAF V600E mutation in tumor specimens prior to initiation of treatment with Vemurafenib. Information on FDA-approved tests for the detection of BRAF V600 mutations in melanoma is available at http://www.fda.gov/CompanionDiagnostics.

Please review the complete therapeutic recommendations that are located here: (3)

## Nomenclature for Selected Alleles

### Selected BRAF variants

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
V600E | p.Val600Glu | NM_004333.4:c.1799T>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/13961/) | NP_004324.2:p.Val600Glu (https://www.ncbi.nlm.nih.gov/clinvar/variation/13961/) | rs113488022 (https://www.ncbi.nlm.nih.gov/snp/rs113488022)
V600K | p.Val600Lys | NM_004333.4:c.1798_1799delGTinsAA (https://www.ncbi.nlm.nih.gov/clinvar/variation/375941/) | NP_004324.2:p.Val600Lys (https://www.ncbi.nlm.nih.gov/clinvar/variation/375941/) | rs121913227 (https://www.ncbi.nlm.nih.gov/snp/121913227)

### Selected NRAS variants

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
NRAS G12V | p.Gly12Val | NM_002524.4:c.35G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/40470/) | NP_002515.1:p.Gly12Val (https://www.ncbi.nlm.nih.gov/clinvar/variation/40470/) | rs121913237 (https://www.ncbi.nlm.nih.gov/snp/121913237)
NRAS G13R | p.Gly13Arg | NM_002524.4:c.37G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/13899/) | NP_002515.1:p.Gly13Arg (https://www.ncbi.nlm.nih.gov/clinvar/variation/13899/) | rs121434595 (https://www.ncbi.nlm.nih.gov/snp/121434595)
NRAS Q61R | p.Gln61Arg | NM_002524.4:c.182A>G | NP_002515.1:p.Gln61Arg | rs11554290 (https://www.ncbi.nlm.nih.gov/snp/11554290)
NRAS Q61K | p.Gln61Lys | NM_002524.4:c.181C>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/73058/) | NP_002515.1:p.Gln61Lys (https://www.ncbi.nlm.nih.gov/clinvar/variation/73058/) | rs121913254 (https://www.ncbi.nlm.nih.gov/snp/121913254)

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (HGVS): https://www.hgvs.org/content/guidelines

## Acknowledgments

Version 2.0 (Published September 30, 2025)

The author would like to thank Adil Daud, MD, Director, Melanoma Clinical Research, UCSF Helen Diller Family Comprehensive Cancer Center, San Francisco, CA, USA and Ben Kong, Pharm. D., Clinical Pharmacist, Oregon Health & Science University, Knight Cancer Institute, Portland, Oregon, USA for providing an expert review of this summary.

Version 1.0 (Published August 15, 2017):

The author would like thank Paul B. Chapman, MD, Medical Oncologist and Head of the Melanoma Section Clinical Immunology Service, Memorial Sloan Kettering Cancer Center, New York; Avadhut Joshi, PhD, Clinical Pharmacogenomics Lead, Translational Software, Bellevue, Washington; Matthew Hardison, PhD, FACMG, Director of BioPharma Laboratory, Aegis Sciences Corporation, Nashville, TN; and Pamala A. Pawloski, PharmD, Research Investigator, HealthPartners Institute, Bloomington, MN; for reviewing this summary.

## Version History

Version 2.0 of this article was published on September 30, 2025. This update includes information regarding the indication of vemurafenib for Erdheim-Chester disease with BRAF V600, the evidence drug-drug interactions regarding CYP3A4 inhibitors and inducers, as well as updated variant information for clinically relevant BRAF mutations.

Version 1.0 of this article (Published on August 15, 2017) is available here.

## References

1 Davies, H., G.R. Bignell, C. Cox, P. Stephens, et al., Mutations of the BRAF gene in human cancer. Nature, 2002. 417(6892): p. 949-54.12068308
2 Long, G.V., A.M. Menzies, A.M. Nagrial, L.E. Haydu, et al., Prognostic and clinicopathologic associations of oncogenic BRAF in metastatic melanoma. J Clin Oncol, 2011. 29(10): p. 1239-46.21343559
3 ZELBORAF- vemurafenib tablet, film coated [package insert]. San Francisco, CA: Genentech, I.; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=38eea320-7e0c-485a-bc30-98c3c45e2763.
4 Leveque, D., Off-label use of targeted therapies in oncology. World J Clin Oncol, 2016. 7(2): p. 253-7.27081648
5 Khaddour, K., H. Kurn, and P.M. Zito, Vemurafenib, in StatPearls. 2025: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/30571050.
6 Belley-Cote, E.P., H. Hanif, F. D'Aragon, J.W. Eikelboom, et al., Genotype-guided versus standard vitamin K antagonist dosing algorithms in patients initiating anticoagulation. A systematic review and meta-analysis. Thromb Haemost, 2015. 114(4): p. 768-77.26158747
7 Robert, C., G.V. Long, B. Brady, C. Dutriaux, et al., Nivolumab in previously untreated melanoma without BRAF mutation. N Engl J Med, 2015. 372(4): p. 320-30.25399552
8 Jarab, A.S., W.A. Al-Qerem, L.M. Khdour, Y.A. Mimi, and M.R. Khdour, New emerging treatment options for metastatic melanoma: a systematic review and meta-analysis of skin cancer therapies. Arch Dermatol Res, 2024. 316(10): p. 735.39485529
9 Joshi, U.M., J. Hundal, J.R. Mata, M.D. Schollenberger, et al., Beyond Checkpoint Inhibition: Keeping Therapeutic Options Open. Am Soc Clin Oncol Educ Book, 2025. 45(3): p. e473856.40233298
10 Forschner, A., H. Niessner, J. Bauer, B. Bender, et al., Successful treatment with vemurafenib in BRAF V600K-positive cerebral melanoma metastasis. JAMA Dermatol, 2013. 149(5): p. 642-4.23677116
11 Eroglu, Z. and A. Ribas, Combination therapy with BRAF and MEK inhibitors for melanoma: latest evidence and place in therapy. Ther Adv Med Oncol, 2016. 8(1): p. 48-56.26753005
12 Solit, D.B., L.A. Garraway, C.A. Pratilas, A. Sawai, et al., BRAF mutation predicts sensitivity to MEK inhibition. Nature, 2006. 439(7074): p. 358-62.16273091
13 NCCN Guidelines Version 2.2025 Melanoma: Cutaneous [Cited. Available from https://www.nccn.org/professionals/physician_gls/pdf/cutaneous_melanoma.pdf.
14 Maio, M., K. Lewis, L. Demidov, M. Mandala, et al., Adjuvant vemurafenib in resected, BRAF(V600) mutation-positive melanoma (BRIM8): a randomised, double-blind, placebo-controlled, multicentre, phase 3 trial. Lancet Oncol, 2018. 19(4): p. 510-520.29477665
15 Hecht, M., L. Zimmer, C. Loquai, C. Weishaupt, et al., Radiosensitization by BRAF inhibitor therapy-mechanism and frequency of toxicity in melanoma patients. Ann Oncol, 2015. 26(6): p. 1238-1244.25762352
16 Fisher, R. and J. Larkin, Vemurafenib: a new treatment for BRAF-V600 mutated advanced melanoma. Cancer Manag Res, 2012. 4: p. 243-52.22904646
17 Larkin, J., V. Chiarion-Sileni, R. Gonzalez, J.J. Grob, et al., Combined Nivolumab and Ipilimumab or Monotherapy in Untreated Melanoma. N Engl J Med, 2015. 373(1): p. 23-34.26027431
18 Chapman, P.B., A. Hauschild, C. Robert, J.B. Haanen, et al., Improved survival with vemurafenib in melanoma with BRAF V600E mutation. N Engl J Med, 2011. 364(26): p. 2507-16.21639808
19 Spagnolo, F., P. Ghiorzo, and P. Queirolo, Overcoming resistance to BRAF inhibition in BRAF-mutated metastatic melanoma. Oncotarget, 2014. 5(21): p. 10206-21.25344914
20 McArthur, G.A., P.B. Chapman, C. Robert, J. Larkin, et al., Safety and efficacy of vemurafenib in BRAF(V600E) and BRAF(V600K) mutation-positive melanoma (BRIM-3): extended follow-up of a phase 3, randomised, open-label study. Lancet Oncol, 2014. 15(3): p. 323-32.24508103
21 Nagai, R., M. Ohara, L.H. Cavallari, K. Drozda, et al., Factors influencing pharmacokinetics of warfarin in African-Americans: implications for pharmacogenetic dosing algorithms. Pharmacogenomics, 2015. 16(3): p. 217-25.25712185
22 Nazarian, R., H. Shi, Q. Wang, X. Kong, et al., Melanomas acquire resistance to B-RAF(V600E) inhibition by RTK or N-RAS upregulation. Nature, 2010. 468(7326): p. 973-7.21107323
23 Rizos, H., A.M. Menzies, G.M. Pupo, M.S. Carlino, et al., BRAF inhibitor resistance mechanisms in metastatic melanoma: spectrum and clinical impact. Clin Cancer Res, 2014. 20(7): p. 1965-77.24463458
24 Poulikakos, P.I., Y. Persaud, M. Janakiraman, X. Kong, et al., RAF inhibitor resistance is mediated by dimerization of aberrantly spliced BRAF(V600E). Nature, 2011. 480(7377): p. 387-90.22113612
25 Boutros, A., E.T. Tanda, E. Croce, F. Catalano, et al., Activity and safety of first-line treatments for advanced melanoma: A network meta-analysis. Eur J Cancer, 2023. 188: p. 64-79.37196485
26 Ascierto, P.A., M. Mandala, P.F. Ferrucci, M. Guidoboni, et al., Sequencing of Ipilimumab Plus Nivolumab and Encorafenib Plus Binimetinib for Untreated BRAF-Mutated Metastatic Melanoma (SECOMBIT): A Randomized, Three-Arm, Open-Label Phase II Trial. J Clin Oncol, 2023. 41(2): p. 212-221.36049147
27 Ascierto, P.A., M. Casula, J. Bulgarelli, M. Pisano, et al., Sequential immunotherapy and targeted therapy for metastatic BRAF V600 mutated melanoma: 4-year survival and biomarkers evaluation from the phase II SECOMBIT trial. Nat Commun, 2024. 15(1): p. 146.38167503
28 Atkins, M.B., S.J. Lee, B. Chmielowski, A.A. Tarhini, et al., Combination Dabrafenib and Trametinib Versus Combination Nivolumab and Ipilimumab for Patients With Advanced BRAF-Mutant Melanoma: The DREAMseq Trial-ECOG-ACRIN EA6134. J Clin Oncol, 2023. 41(2): p. 186-197.36166727
29 Sharma, A., S.R. Shah, H. Illum, and J. Dowell, Vemurafenib: targeted inhibition of mutated BRAF for treatment of advanced melanoma and its potential in other malignancies. Drugs, 2012. 72(17): p. 2207-22.23116250
30 Flor, D., M. Pedroso, I. Coutinho, and M. Goncalo, Toxic epidermal necrolysis caused by vemurafenib in a metastatic malignant melanoma. BMJ Case Rep, 2025. 18(2).39956569
31 Oddershede, J.K., I.K. Meklenborg, L. Bastholt, L.M. Guldbrandt, et al., Cardiotoxicity in patients with metastatic melanoma treated with BRAF/MEK inhibitors: a real-world analysis of incidence, risk factors, and reversibility. Acta Oncol, 2025. 64: p. 507-515.40223207
32 Yu, Q., J. Xie, J. Li, Y. Lu, and L. Liao, Clinical outcomes of BRAF plus MEK inhibition in melanoma: A meta-analysis and systematic review. Cancer Med, 2019. 8(12): p. 5414-5424.31393083
33 Drews, M.A., A. Baumgarten, S. Zensen, M. Opitz, et al., Adverse effects of systemic advanced melanoma therapies-do BRAF/MEK inhibitors increase the incidence of mesenteric panniculitis? Eur Radiol, 2025.40310541
34 Qazi, M.S., A. Ahmad, M. Mukhtiar, R. Noor, et al., Neurological manifestations of Erdheim-Chester disease and their management: A scoping review. Medicine (Baltimore), 2025. 104(12): p. e41932.40128017
35 Haroche, J., F. Cohen-Aubart, and Z. Amoura, Erdheim-Chester disease. Blood, 2020. 135(16): p. 1311-1318.32107533
36 Campochiaro, C., A. Tomelleri, F. Catamero, F. Pegoraro, et al., Anakinra improves retention rate of targeted treatments in Erdheim-Chester disease. Rheumatology (Oxford), 2025.
37 Agrawal, A.K., P. Borah, P.D. Rath, and R. Naithani, Very low-dose vemurafenib maintenance for cardiac Erdheim Chester disease. Blood Res, 2025. 60(1): p. 25.40214901
38 Orlandi, A., A. Calegari, A. Inno, R. Berenato, et al., BRAF in metastatic colorectal cancer: the future starts now. Pharmacogenomics, 2015. 16(18): p. 2069-81.26615988
39 Weinstein, I.B. and A.K. Joe, Mechanisms of disease: Oncogene addiction--a rationale for molecular targeting in cancer therapy. Nat Clin Pract Oncol, 2006. 3(8): p. 448-57.16894390
40 Goyal, G., M.L. Heaney, M. Collin, F. Cohen-Aubart, et al., Erdheim-Chester disease: consensus recommendations for evaluation, diagnosis, and treatment in the molecular era. Blood, 2020. 135(22): p. 1929-1945.32187362
41 Sarkozy, A., C. Carta, S. Moretti, G. Zampino, et al., Germline BRAF mutations in Noonan, LEOPARD, and cardiofaciocutaneous syndromes: molecular diversity and associated phenotypic spectrum. Hum Mutat, 2009. 30(4): p. 695-702.19206169
42 Koudova, M., E. Seemanova, and M. Zenker, Novel BRAF mutation in a patient with LEOPARD syndrome and normal intelligence. Eur J Med Genet, 2009. 52(5): p. 337-40.19416762
43 Mandal, R., S. Becker, and K. Strebhardt, Stamping out RAF and MEK1/2 to inhibit the ERK1/2 pathway: an emerging threat to anticancer therapy. Oncogene, 2016. 35(20): p. 2547-61.26364606
44 Puerta-Garcia, E., M. Canadas-Garre, and M.A. Calleja-Hernandez, Molecular biomarkers in colorectal carcinoma. Pharmacogenomics, 2015. 16(10): p. 1189-222.26237292
45 Ekedahl, H., H. Cirenajwis, K. Harbst, A. Carneiro, et al., The clinical significance of BRAF and NRAS mutations in a clinic-based metastatic melanoma cohort. Br J Dermatol, 2013. 169(5): p. 1049-55.23855428
46 Fedorenko, I.V., G.T. Gibney, V.K. Sondak, and K.S. Smalley, Beyond BRAF: where next for melanoma therapy? Br J Cancer, 2015. 112(2): p. 217-26.25180764
47 Edlundh-Rose, E., S. Egyhazi, K. Omholt, E. Mansson-Brahme, et al., NRAS and BRAF mutations in melanoma tumours in relation to clinical characteristics: a study based on mutation screening by pyrosequencing. Melanoma Res, 2006. 16(6): p. 471-8.17119447
48 Johnson, D.B. and I. Puzanov, Treatment of NRAS-mutant melanoma. Curr Treat Options Oncol, 2015. 16(4): p. 15.25796376
49 Johnson, D.B., C.M. Lovly, M. Flavin, K.S. Panageas, et al., Impact of NRAS mutations for patients with advanced melanoma treated with immune therapies. Cancer Immunol Res, 2015. 3(3): p. 288-95.25736262
50 Moschos, S.J., War against NRAS-Mutant Melanoma Using Targeted Therapies Remains Challenging. Clin Cancer Res, 2022. 28(14): p. 2977-2979.35587446
51 Randic, T., I. Kozar, C. Margue, J. Utikal, and S. Kreis, NRAS mutant melanoma: Towards better therapies. Cancer Treat Rev, 2021. 99: p. 102238.34098219
52 Pharmacogene Variation Consortium [Internet]. CYP3A4 [Cited June 9, 2025]. Available from https://www.pharmvar.org/gene/CYP3A4.
53 Westlind-Johnsson, A., R. Hermann, A. Huennemeyer, B. Hauns, et al., Identification and characterization of CYP3A4*20, a novel rare CYP3A4 allele without functional activity. Clin Pharmacol Ther, 2006. 79(4): p. 339-49.16580902
54 Apellaniz-Ruiz, M., L. Inglada-Perez, M.E. Naranjo, L. Sanchez, et al., High frequency and founder effect of the CYP3A4*20 loss-of-function allele in the Spanish population classifies CYP3A4 as a polymorphic enzyme. Pharmacogenomics J, 2015. 15(3): p. 288-92.25348618
55 Werk, A.N., S. Lefeldt, H. Bruckmueller, G. Hemmrich-Stanisak, et al., Identification and characterization of a defective CYP3A4 genotype in a kidney transplant patient with severely diminished tacrolimus clearance. Clin Pharmacol Ther, 2014. 95(4): p. 416-22.24126681
56 Wang, D., Y. Guo, S.A. Wrighton, G.E. Cooke, and W. Sadee, Intronic polymorphism in CYP3A4 affects hepatic expression and response to statin drugs. Pharmacogenomics J, 2011. 11(4): p. 274-86.20386561
57 Dutch Pharmacogenetics Working Group. Pharmacogenetics, General background information - CYP3A4 English. 2021 June 6, 2025]; Available from: https://www.knmp.nl/sites/default/files/2023-11/CYP3A4_English.pdf.
58 ALFA: Allele Frequency Aggregator. [Cited June 6, 2025]. Available from www.ncbi.nlm.nih.gov/snp/docs/gsr/alfa/
59 Yates, A.D., P. Achuthan, W. Akanni, J. Allen, et al., Ensembl 2020. Nucleic Acids Res, 2020. 48(D1): p. D682-D688.31691826
60 Sahadudheen, K., M.R. Islam, and M. Iddawela, Long Term Survival and Continued Complete Response of Vemurafenib in a Metastatic Melanoma Patient with BRAF V600K Mutation. Case Rep Oncol Med, 2016. 2016: p. 2672671.26989536
61 Raaijmakers, M.I., D.S. Widmer, A. Narechania, O. Eichhoff, et al., Co-existence of BRAF and NRAS driver mutations in the same melanoma cells results in heterogeneity of targeted therapy resistance. Oncotarget, 2016. 7(47): p. 77163-77174.27791198
62 Seth, R., S.S. Agarwala, H. Messersmith, K.C. Alluri, et al., Systemic Therapy for Melanoma: ASCO Guideline Update. J Clin Oncol, 2023. 41(30): p. 4794-4820.37579248
63 Swetter, S.M., H. Tsao, C.K. Bichakjian, C. Curiel-Lewandrowski, et al., Guidelines of care for the management of primary cutaneous melanoma. J Am Acad Dermatol, 2019. 80(1): p. 208-250.30392755
64 Salzmann, M., J. Pawlowski, C. Loquai, D.A. Rafei-Shamsabadi, et al., MEK inhibitors for pre-treated, NRAS-mutated metastatic melanoma: A multi-centre, retrospective study. Eur J Cancer, 2022. 166: p. 24-32.35272084
65 Dinter, L., P.C. Karitzky, A. Schulz, A.A. Wurm, et al., BRAF and MEK inhibitor combinations induce potent molecular and immunological effects in NRAS-mutant melanoma cells: Insights into mode of action and resistance mechanisms. Int J Cancer, 2024. 154(6): p. 1057-1072.38078628
66 US Food & Drug Administration. Nucleic Acid Based Tests. 2025 March 5, 2025 June 6, 2025]; Available from: https://www.fda.gov/medical-devices/in-vitro-diagnostics/nucleic-acid-based-tests.

## Related Summaries by Gene

Cetuximab Therapy and RAS and BRAF Genotype

Dabrafenib Therapy and BRAF Genotype

Panitumumab Therapy and RAS and BRAF Genotype

## Related Summaries by Drug Class

Dabrafenib Therapy and BRAF Genotype

## Tests in GTR by Gene

NRAS gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=4893[geneid])

BRAF gene (https://www.ncbi.nlm.nih.gov/gtr/tests/?term=673[geneid])