# Valbenazine Therapy and CYP2D6 Genotype

## Introduction

Valbenazine (marketed as Ingrezza in the US and Dysval in Japan) is a vesicular monoamine transporter 2 (VMAT2) inhibitor used in the treatment of tardive dyskinesia (TD) or Huntington disease (HD) chorea (1, 2). Valbenazine and its active metabolite inhibit the transporter protein that packages neurotransmitters into synaptic vesicles, reducing uncontrollable movements attributed to dopamine receptor hypersensitivity and other synaptic dysfunction. The active valbenazine metabolite is further metabolized into inactive compounds by cytochrome P450 (CYP450) family enzymes, including the CYP2D6 protein.

Individuals with no CYP2D6 enzymatic activity (poor metabolizers [PMs]) will have a higher exposure to valbenazine and its active metabolite, which can increase the risk of exposure-related adverse reactions (1). Therefore, the US FDA-approved label recommends that known CYP2D6 PMs take no more than 40 mg valbenazine daily. Individuals with other metabolizer phenotypes may take up to 80 mg daily, with dosing based on individual symptoms and tolerability (Table 1) (1). Notably, the FDA also advises the same lower dose for individuals taking a strong CYP2D6 inhibitor (1).

The FDA-approved label further cautions that individuals with HD are at increased risk for depression and suicidal ideation or behavior, particularly with VMAT2 inhibitor therapy (1). The recommended dosing in this population follows a slower titration time scale than for TD, with dose increases of 20 mg every 2 weeks until either efficacy is achieved, or the maximum tolerated dose is reached.

Table 1:

Statement on CYP2D6-based Dosing of Valbenazine from the Food and Drug Administration (FDA, 2024)

CYP2D6 status | Effect | Recommendation
PM | Increased exposure to valbenazine and active metabolite | 40 mg daily maximum dose
Non-PM, no inhibitory medications | Normal metabolism | Initial dose of 40 mg daily Increase to 80 mg after one week for TD; increase in 20 mg increments every 2 weeks for HD up to 80 mg (consider 40 mg or 60 mg based on response and tolerability)
Non-PM, strong CYP2D6 inhibitor co-medication | Increased exposure to valbenazine and active metabolite | 40 mg daily maximum dose

PM: Poor metabolizer; TD: Tardive dyskinesia; HD: Huntington disease

Table adapted from (1).

## Drug: Valbenazine

Valbenazine, also known as Ingrezza, is a reversible inhibitor of VMAT2 indicated for the treatment of adults with TD or chorea associated with HD (1). For TD, valbenazine is initially dosed at 40 mg per day, which may be increased to 80 mg daily after one week, with an option to dose at 40 or 60 mg based on response and tolerability (1). For HD chorea, dosing also begins at 40 mg once daily, but should be titrated in 20 mg increments every 2 weeks up to 80 mg, with lower doses of 40 or 60 mg considered based on response and tolerability (1). Valbenazine was also investigated as a treatment for tics associated with Tourette syndrome; however, it did not meet primary efficacy outcome measures (3). In Japan, valbenazine is approved to treat TD as valbenazine tosilate (brand name Dysval) and is dosed at 40–80 mg daily, adjusted based on individual symptoms (2).

Valbenazine belongs to the broader class of VMAT2 inhibitors, which facilitate the packaging of neurotransmitters and other monoamines into vesicles, enabling controlled release through vesicle fusion with the plasma membrane. The VMAT2 protein is expressed in neurons, neuroendocrine cells, platelets, and mast cells, and has high affinity for histamine, serotonin, norepinephrine, and dopamine (4). Inhibition of VMAT2 activity reduces dopaminergic signaling in the brain by decreasing dopamine availability for synaptic vesicle release.

Both valbenazine and deutetrabenazine are structurally related to tetrabenazine, differing only in chemical modifications that enhance stability. The active metabolite of all 3 medications is [+]-alpha-dihydrotetrabenazine ([+]-alpha-HTBZ). Compared with other VMAT2 inhibitors, valbenazine is metabolized more slowly via hydrolysis of a valine ester, reaching peak concentration within 1–1.5 hours after dosing, with a systemic half-life of approximately 20 hours (5). The formation of [+]-alpha-HTBZ is delayed, with peak concentrations reached 4–9 hours after dosing and a half-life similar to the parent compound (15–20 hours) (1, 5). Another metabolite, NBI-136110, is also formed from valbenazine but has much lower affinity for VMAT2 than [+]-alpha-HTBZ (6). Studies indicate that valbenazine’s pharmacokinetic parameters are similar in individuals from North America (European or African) and East Asian (Korean) descent (7). Beyond hydrolysis, CYP450 enzymes contribute to valbenazine metabolism, CYP3A4/5 enzymes form mono-oxidized valbenazine and [+]-alpha-HTBZ is metabolized by CYP2D6 (1). Higher exposure to valbenazine and [+]-alpha-HTBZ may increase the risk of exposure-related adverse reactions (1).

Significant adverse effects of valbenazine include depression, suicidal ideation in individuals with HD, hypersensitivity reactions, somnolence, QT prolongation, neuroleptic malignant syndrome (NMS) and Parkinsonism (1). One analysis of adverse events reported to the FDA suggests that females may have a moderately higher likelihood of serious adverse reactions than males in response to valbenazine therapy (8). This analysis also found a high reporting odds ratio for neurological adverse events, including drooling, dyskinesia, bradykinesia, and slow speech (8).

Depression and suicidal ideation have been reported in clinical trials and real-world data for VMAT2 inhibitors. The FDA-approved drug label includes a black box warning for depression and suicidal ideation in HD treatment, recommending extra caution when treating individuals with a history of depression, suicidal behavior (1). Suicidal ideation was significantly associated with this VMAT2 inhibitors in an analysis of data from the FDA Adverse Event Reporting System (FAERS), likely due to underlying psychiatric conditions in this population. There was no significant association between valbenazine use and suicidal behavior (9). Another analysis of FAERS data confirmed an association of VMAT2 inhibitors with suicidal ideation, but increased odds of suicidal behavior were not observed with valbenazine or deutetrabenazine (9).

Hypersensitivity reactions, including angioedema affecting the larynx, glottis, lips and eyelids, or urticaria and rash may occur; treatment should be discontinued if these reactions occur (1). It is unlikely that the reported angioedema event from the KINECT-HD clinical trial was caused by the medication, but rather a food allergy unrelated to the medication or its ingredients (10). Somnolence, sedation, or excessive sleepiness were common adverse reactions observed during clinical trials. Individuals should avoid activities requiring alertness until they know their response to valbenazine (1, 11, 12).

Elongation of the QT interval of the cardiac rhythm may occur though it is unlikely to be clinically significant at recommended doses. Individuals at higher risk for clinically significant QT elongation include those on strong CYP2D6 or CYP3A4 inhibitors or those with reduced CYP2D6 activity due to genetic variation (PMs). Individuals with genetic or pharmacologically reduced CYP2D6 or CYP3A4 activity may require a reduced dose of 40 mg daily (1). Those with underlying long QT syndrome or arrhythmia should avoid valbenazine (1).

The symptoms of NMS include hyperpyrexia, muscle rigidity, altered mental status, and autonomic instability such as tachycardia (1). This complex of symptoms is potentially fatal and can be difficult to diagnose. If NMS is suspected, immediately discontinue valbenazine, and symptomatic treatment and medical monitoring for NMS as well as any concomitant serious medical problems should begin. Recurrent NMS has been reported after resumption of valbenazine therapy; individuals should be monitored carefully. (1)

Parkinsonism may also develop with VMAT2 inhibitor therapy (13), observed in 4.7% of HD trials (compared to 0% with placebo) and in post-marketing reports for TD use (1, 8, 14, 15). The Parkinson-like symptoms may be more disruptive daily routines and functional abilities than untreated HD or TD, and dose reduction or discontinuation of valbenazine is recommended in cases of clinically significant symptoms. (1)

There is limited data on drug-associated risks for valbenazine use in pregnant or lactating women. Animal studies showed increased stillbirths in rat pups when the mother received valbenazine during pregnancy, though no malformations were observed in the live littermates; a risk to human viability during pregnancy is possible (1). No data exists regarding valbenazine or metabolites in human breast milk, or the impact on breastfed infants. Based on animal studies, valbenazine compounds may be transferred into breast milk, potentially at concentrations higher than in plasma (1). Women are advised not to breastfeed during valbenazine treatment or for 5 days after the final dose (1, 16). Valbenazine has not been established as safe or effective in a pediatric population (1). However, there is off-label use of valbenazine and other VMAT2 inhibitors to manage NKX2-1 related disorders with chorea in both children and adults (17).

No dose adjustment is required for elderly individuals (1). A pooled analysis of 6-week randomized, placebo-controlled trials (KINECT, KINECT 2, and KINECT 3) and long-term clinical trials (KINECT 3 extension and KINECT 4) showed no difference in response rates or adverse events between study participants under 55 and those aged 55 and older (18). One analysis of the FDA adverse event reporting data for valbenazine showed a higher probability for neurological adverse events in middle-aged adults (18–64 years of age) compared to elderly adults (65+), possibly attributed to the higher incidence of schizophrenia in this age group (8). A post-hoc analysis of the J-KINECT study found that treatment emergent adverse events led to a higher discontinuation rate in elderly participants compared to younger participants, though overall adverse event types and incidence were similar between groups (19).

No dosage adjustment is needed for individuals with renal impairment (1). However, for individuals with moderate or severe hepatic impairment, a dose reduction is recommended to prevent increased exposure to valbenazine [+]-alpha-HTBZ (1).

### Tardive Dyskinesia

Tardive dyskinesia is a medication-induced movement disorder. These movements are involuntary and repetitive, most commonly affecting the tongue, mouth, jaw, and face, but also potentially affecting the limbs and trunk. Severe cases are associated with difficulty speaking and swallowing, and the condition can be disfiguring and stigmatizing, significantly impacting quality of life (20).

Tardive dyskinesia is caused by medicines that block dopamine receptors, including antipsychotics (for example, aripiprazole, clozapine, risperidone, thioridazine) and antiemetic drugs used to treat nausea and vomiting (such as metoclopramide and prochlorperazine). Tardive dyskinesia can be irreversible and lifelong, persisting even after the causative medicine has been stopped (21). Studies indicate that PM or ultra-rapid metabolizer (UM) CYP2D6 phenotype individuals on antipsychotic therapy are more likely to have an Abnormal Involuntary Movement Scale (AIMS) score indicative of TD, with PMs experiencing more severe TD (22). The increased TD severity may be due to altered drug metabolism.

Approximately 25% of individuals treated with antipsychotics develop TD, though it is more common with first-generation than second-generation antipsychotics (23). Tardive syndromes, including TD, affect up to one-third of individuals with schizophrenia treated with antipsychotics (24). Initially, the prevalence of TD was expected to decrease as newer antipsychotics were developed that are less likely to cause TD. However, TD remains prevalent, partly because the newer antipsychotics have expanded indications, including depression, bipolar disorder, personality disorder, irritability in autism spectrum disorder, as well as off-label uses including insomnia and anxiety. Consequently, the population at risk for TD has increased (25, 26, 27, 28). This population may also include children or adolescents on antipsychotics, with a TD prevalence between 5–20% based on a review of thirteen studies (29).

Because TD is irreversible, prevention is crucial, requiring both limited use of drugs that may cause TD and early diagnosis (30, 31). While not a cure, valbenazine and related VMAT2 inhibitors have been shown to reduce the abnormal movements associated with TD and are generally well tolerated. However, there are no head-to-head comparisons between VMAT2 inhibitors, and TD symptoms return approximately 4 weeks after treatment is discontinued (23, 24, 26, 30, 32, 33, 34, 35).

Several genetic loci have been linked to TD risk in response to antipsychotic therapy (36). In addition to CYP2D6, the CYP1A2 locus variation is associated with more frequent limb-truncal TD, and environmental factors such as smoking may additively impact CYP1A2 protein expression and further influence TD presentation (37). Variants in dopamine signaling pathways (specifically DRD2 and DRD3) and serotonin systems (HTR2A) have also been associated with TD development (38, 39, 40, 41). Notably, the association with COMT (encoding catechol-O-methyltransferase, a dopamine metabolizing enzyme) and TD risk appears specific to females (42). Variants in HSPG2 have been associated with TD in both Japanese and European ancestry cohorts (43, 44). Additionally, variation in SLC18A2, which encodes VMAT2, has been associated with TD risk or protection (discussed further below).

## Gene: CYP2D6

The CYP450 family is a large and diverse group of enzymes that form the major system for metabolizing lipids, hormones, toxins, and drugs in the liver. The CYP450 genes are highly polymorphic, resulting in decreased, absent, or increased enzyme activity. One prominent CYP450 member, CYP2D6, is responsible for the metabolism of many commonly prescribed drugs, including antidepressants, antipsychotics, analgesics, and beta-blockers.

### The CYP2D6 Alleles

The CYP2D6 gene is highly polymorphic, with over 170 star (*) alleles described and cataloged by the Pharmacogene Variation (PharmVar) Consortium, each associated with either normal, decreased, absent, or uncertain enzyme function (Table 2) (45, 46). Star alleles are defined by the variants detected on a single chromosome (haplotype).

An individual’s combination of CYP2D6 haplotypes determines their diplotype (for example, CYP2D6 *4/*4). Based on their impact on enzyme function, each allele is assigned an activity score from 0 to 1, which is then used to assign a phenotype (for example, CYP2D6 PM). However, the activity score system is not standardized across all clinical laboratories or CYP2D6 genotyping platforms, resulting in some variability. To promote consistency, the Clinical Pharmacogenetics Implementation Consortium (CPIC) and Dutch Pharmacogenetics Working Group (DPWG) standardized their CYP2D6 genotype-to-phenotype methods in 2019, creating a consensus activity scoring guideline. The CYP2D6 phenotype is predicted from the diplotype activity score, defined by the sum of the allele score values, which typically ranges from 0 to 3.0: (47)

- A UM has an activity score greater than 2.25
- A normal metabolizer (NM) has an activity score of 1.25–2.25
- An intermediate metabolizer (IM) has an activity score of >0–<1.25
- A PM has an activity score of 0

Table 2.

Activity Status of Selected CYP2D6 Alleles

Allele type | CYP2D6 alleles | Activity score
Normal function | *1, *2, *27, *33 | 1
Decreased function | *17, *41, *49 | 0.5
Strongly decreased function | *10 | 0.25
No function | *3, *4, *5, *6, *36 | 0

For a comprehensive list of CYP2D6 alleles, please See the Pharmacogene Variation Consortium (https://www.pharmvar.org/gene/CYP2D6). Activity scores from (48).

The CYP2D6*1 allele is the wild-type allele when no variants are detected and is associated with normal enzyme activity and the NM phenotype. The CYP2D6*2, *27, and *33 alleles are also considered to have near-normal activity. Other CYP2D6 alleles include variants that produce non-functioning enzymes (for example, *3, *4, and *6) (49, 50, 51) or enzymes with decreased activity (for example, *10, *17, and *41) (46, 52) (see Table 2). There are notable interethnic differences in allele frequency, with *3, *4, *6, and *41 being more common in individuals of European ancestry, *17 more common in African ancestry, and *10 more common in Asian ancestry. (53)

Larger structural variants at the CYP2D6 locus, including gene duplications, deletions, tandem alleles, gene hybrids, and gene conversions have also been described (54). Deletions result in no-function alleles (for example, the *5 allele). Duplications have been reported for alleles with normal, decreased, and no function. In cases of allele duplications, the activity scores of all CYP2D6 alleles are summed to predict the metabolizer phenotype. Additional details on structural variants are available from PharmVar (see the document Structural Variation for CYP2D6) (55).

The frequency of the CYP2D6 star alleles with altered function varies among global populations, resulting in different metabolizer phenotype frequencies. Given CYP2D6’s role in the drug metabolism, the literature on allele and phenotype frequency is expansive. Most populations have a high frequency of normal-function star alleles, resulting in a high proportion of NMs. However, reduced-function alleles like CYP2D6*10 are highly prevalent in East Asian populations, leading to a higher proportion of IMs. Many groups in sub-Saharan Africa have higher frequencies of decreased-function alleles like CYP2D6*17 and *29, correlating with lower CYP2D6 activity scores. Additional information on allele and phenotype frequencies is available in the CYP2D6 supplemental chapter.

Pharmacologic Conversion of CYP2D6 Phenotype

Factors other than genotype can affect CYP2D6 enzyme activity and, thus the metabolizer phenotype of any individual. Administration of an interacting medication can lead to a phenomenon called phenoconversion, in which an individual with one metabolizer genotype exhibits the enzymatic activity of a different metabolizer group (either higher or lower, depending on the medications). Studies indicate that 17–25% of individuals are impacted by phenoconversion (56).

The enzymatic activity of CYP2D6 can be inhibited by medications including strong inhibitors such as paroxetine, fluoxetine, bupropion, and quinidine, as well as moderate inhibitors like duloxetine (57, 58, 59, 60). This can potentially result in NMs or IMs responding to medications as if they were PMs, depending on the inhibitor’s strength. Strong inhibitors can completely inhibit CYP2D6, while moderate inhibitors can reduce its activity by 50%. Therefore, co-medication of multiple CYP2D6 strong or moderate inhibitors may reduce the metabolism of drug substrates, as observed in psychiatric pharmacotherapy (61, 62). In contrast, discontinuing a concomitant CYP2D6 inhibitor may allow an individual's CYP2D6 activity to revert to their genetically predicted baseline phenotype.

Integration of CYP2D6 phenoconversion into clinical practice requires knowledge of multiple clinical factors, and tools have been developed to support clinicians in this integration (63).

### Other Genes of Interest: SLC18A2

The gene SLC18A2 is a member of the solute carrier family and encodes VMAT2. Bi-allelic loss-of-function alleles in SLC18A2 cause brain vesicular monoamine transport disease, also known as Parkinsonism-dystonia 2, infantile-onset, a movement disorder that presents similarly to cerebral palsy (64, 65, 66, 67, 68, 69, 70). Symptoms of brain vesicular monoamine transport disease include global developmental delay, intellectual disability, truncal hypotonia, dystonia, and oculogyric crises, among other findings (70).

The SLC18A2 locus has also been linked with TD, with variants either increasing risk for (rs2015586) or protecting against (rs363224) TD (71, 72). Variation in SLC18A2 has been reported in healthy individuals, though variants leading to a change in the amino acid sequence (2 missense variants in SLC18A2) are notably rarer than SLC6A4 (SERT, 9 missense variants) (73). Analysis of the 4 variants identified in one study showed only one variant had notable difference (though it was non-significant) on valbenazine interaction with the VMAT2 protein, a substitution of threonine (Thr) at amino acid 249 for methionine (Met) (rs534529508; NM_003054.6:c.746C>T; NP_003045.2:p.Thr249Met). This variant was also identified in a cohort of individuals with Parkinson disease (73). Additional studies may be warranted to determine if SLC18A2 variants are associated with response to VMAT2 inhibitors, including efficacy or adverse effects such as parkinsonism.

## Linking CYP2D6 Genetic Variation with Treatment Response

The role of CYP2D6 in valbenazine metabolism is largely based on the established metabolism of [+]-alpha-HTBZ by CYP2D6. A small clinical study demonstrated that CYP2D6 PMs (n=25) had approximately a 2-fold higher exposure to [+]-alpha-HTBZ than NM (1, 5). Analysis of IMs (n=7) indicated only a 22% increase in exposure compared to NMs and was deemed clinically insignificant (1). Additionally, inhibition of CYP2D6 enzymatic activity by paroxetine co-medication also led to increased [+]-alpha-HTBZ exposure in otherwise healthy individuals (74).

The frequency of CYP2D6 PMs is lower in East Asian populations than in the North American population included in the KINECT clinical trials, prompting a separate study of CYP2D6 IM phenotype and valbenazine pharmacokinetics in a Korean population (7). This study reported similar plasma concentrations of [+]-alpha-HTBZ (also referred to as NBI-98782) between NM and IM participants (7). Another study based in Japan (J-KINECT) examined treatment response in a cohort of Japanese ancestry and found similar rates of improvement (measured as a decrease in AIMS score) and adverse reactions as compared to the KINECT studies (12, 75). Based on pharmacokinetics and metabolism data, CYP2D6 PMs are advised to take no more than 40 mg daily per the Pharmaceuticals and Medical Devices Agency (Japan) review (2).

## Genetic Testing

The NIH Genetic Testing Registry (GTR) includes tests for CYP2D6 (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=1565%5bgeneid%5d) and valbenazine response (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=CN282579). The available CYP2D6 tests include targeted single-gene tests to multi-gene panels. In addition, the Association for Molecular Pathology (AMP) has recommended a panel of variant CYP2D6 alleles to include in clinical genotyping assays (76). For CYP2D6, the AMP recommends that the minimum panel of variant alleles should include *2, *3, *4, *5, *6, *9, *10, *17, *29, *41, and copy number interrogation.

Results are reported as a diplotype, such as CYP2D6 *1/*1, and copy number testing is very important when interpreting CYP2D6 results (77). When individuals have more than 2 copies of CYP2D6, the copies of the allele are denoted by an “xN”, where the “N” can either be quantified or unquantified (for example, CYP2D6*1/*2x2 or CYP2D6 *1/*2xN). Some laboratories also use “DUP” to indicate an increase in copy number, though reports may not always specify the number of duplications or the allele that has been duplicated due to technical limitations. Test results may include an interpretation of the individual’s predicted metabolizer phenotype, which can be verified by checking the diplotype and calculating the CYP2D6 activity score as described in the “CYP2D6 Alleles” section. Consideration of the detected alleles is important when interpreting test reports that do not specify which allele is duplicated or how many copies are present, as the activity score can vary if the DUP allele has decreased or no function.

Studies have reported successful implementation of pharmacogenetic testing to guide medication selection and dosing in a clinical setting (78, 79, 80). Of particular concern are cases where individuals are on multiple medications for chronic conditions, where gene–drug or gene–drug–drug interactions can significantly affect medication response (81).

## The CYP2D6 Gene Interactions with Medications Used for Additional Indications

The CYP enzyme family is involved in the metabolism of many substances, with CYP2D6 being implicated in altered pharmacologic responses for many compounds. The drugs can be categorized into many different classes:

- Antipsychotics—for example, aripiprazole, risperidone, thioridazine and—to a lesser extent—clozapine is metabolized by CYP2D6. The FDA recommends the aripiprazole dosage should be reduced in PMs and contraindicates thioridazine in individuals with reduced CYP2D6 activity due to increased risk of potentially fatal side effects. The UMs may have a decreased plasma concentration of risperidone, per DPWG recommendations.
- Tricyclic antidepressants—for example, amitriptyline, and imipramine may require dosage adjustments, potentially guided by therapeutic drug monitoring, to achieve therapeutic range in UMs or PMs. Tricyclic antidepressants may be ineffective in CYP2D6 UMs, depending on the indication and dosage used.
- Serotonin and norepinephrine reuptake inhibitors—for example atomoxetine and venlafaxine may have reduced efficacy in UMs at standard doses, while PMs are at risk of elevated plasma concentrations. The Dutch Pharmacogenetics Working Group advises against venlafaxine in CYP2D6 PMs and IMs.
- Cardiovascular dysfunction—for example, carvedilol, metoprolol, and propafenone are metabolized by CYP2D6. The PMs may have higher plasma concentrations compared with NMs, resulting in potentially undesired side effects or (in the case of metoprolol) extensive slowing of the heart rate.
- Anticancer medications—for example, tamoxifen is activated by CYP2D6, and IMs or PMs may have reduced benefit from tamoxifen therapy.
- Pain management—for example, codeine and tramadol are prodrugs that require activation by CYP2D6 to achieve the desired analgesic effect.
- Various therapies for genetic disorders—for example eliglustat used to treat Gaucher disease, and deutetrabenazine, used in HD, have reduced dose recommendations for CYP2D6 PMs. The CYP2D6 UMs may not achieve adequate concentrations of eliglustat, making CYP2D6 genotyping necessary before initiating eliglustat therapy.

It is important to note that CYP2D6 is the most referenced biomarker in FDA drug labels; thus, the list provided here is not exhaustive. Additional information on CYP2D6 gene–drug interactions are available from ClinPGx (https://www.clinpgx.org/gene/PA128), CPIC (https://cpicpgx.org/genes-drugs/) and the FDA (https://www.fda.gov/drugs/science-and-research-drugs/table-pharmacogenomic-biomarkers-drug-labeling) (search for “CYP2D6”).

## Therapeutic Recommendations based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

2024 Statement from the US Food and Drug Administration (FDA):

The recommended dosage for known CYP2D6 poor metabolizers is [valbenazine] 40 mg once daily.

[…]

The recommended dosage for patients receiving strong CYP2D6 inhibitors is [valbenazine] 40 mg once daily.

[…]

Dosage reduction of [valbenazine] is recommended for known CYP2D6 poor metabolizers. Increased exposure (C_max_ and AUC) to valbenazine’s active metabolite was observed in CYP2D6 poor metabolizers. Increased exposure of active metabolite may increase the risk of exposure-related adverse reactions.

Please review the complete therapeutic recommendations that are located here: (1).

## Nomenclature of Selected CYP2D6 Alleles

Common allele name | Alternative names | HGVS reference sequence | | dbSNP reference identifier for allele location
Common allele name | Alternative names | Coding | Protein | dbSNP reference identifier for allele location
CYP2D6*2^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*2^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*3^[1]^ | 2550delA | NM_000106.6:c.775del (https://www.ncbi.nlm.nih.gov/clinvar/variation/16894) | NP_000097.3:p.Arg259fs | rs35742686 (https://www.ncbi.nlm.nih.gov/snp/rs35742686)
CYP2D6*4^[1]^ | 1846G>A | NM_000106.6:c.506-1G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/16889/) | Variant occurs in a non-coding region (splice variant causes a frameshift) | rs3892097 (https://www.ncbi.nlm.nih.gov/snp/rs3892097)
CYP2D6*5^[1]^ | Gene deletion (https://www.ncbi.nlm.nih.gov/clinvar/variation/16890/)
CYP2D6*6^[1]^ | 1707 del T | NM_000106.6:c.454delT (https://www.ncbi.nlm.nih.gov/clinvar/variation/16891/) | NP_000097.3:p.Trp152Glyfs | rs5030655 (https://www.ncbi.nlm.nih.gov/snp/rs5030655)
CYP2D6*7^[2]^ | 2936A>C | NM_000106.6:c.971A>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385) | NP_000097.3:p.His324Pro | rs5030867 (https://www.ncbi.nlm.nih.gov/snp/rs5030867)
CYP2D6*8^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*8^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*8^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*9^[1]^ | 2616delAAG | NM_000106.6:c.841_843del (https://www.ncbi.nlm.nih.gov/clinvar/variation/617719) | NP_000097.3:p.Lys281del | rs5030656 (https://www.ncbi.nlm.nih.gov/snp/rs5030656)
CYP2D6*10^[1]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*10^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*17^[1]^ | 1022C>T | NM_000106.6:c.320C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39379/) | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D6*17^[1]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*17^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840/)
CYP2D6*12^[2]^ | 124G>A | NM_000106.6:c.124G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39387/) | NP_000097.3:p.Gly42Arg | rs5030862 (https://www.ncbi.nlm.nih.gov/snp/rs5030862)
CYP2D6*12^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*12^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*14^[2]^ | 1759G>T | NM_000106.6:c.505G>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/39385/) | NP_000097.3:p.His324Pro | rs5030865 (https://www.ncbi.nlm.nih.gov/snp/rs5030865)
CYP2D6*14^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*14^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*15^[2]^ | 137_138insT | NM_000106.6:c.137dup (https://www.ncbi.nlm.nih.gov/clinvar/variation/678343) | NP_000097.3:p.Leu47fs | rs774671100 (https://www.ncbi.nlm.nih.gov/snp/rs774671100)
CYP2D6*21^[2]^ | 2580_2581insC | NM_000106.5:c.805dup | NP_000097.3:p.Arg269fs | rs72549352 (https://www.ncbi.nlm.nih.gov/snp/rs72549352)
CYP2D6*21^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*21^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*28 | 19G>A | NM_000106.6:c.19G>A | NP_000097.3:p.Val7Met | rs72549358 (https://www.ncbi.nlm.nih.gov/snp/rs72549358)
CYP2D6*28 | 1705C>G | NM_000106.6:c.451C>G | NP_000097.3:p.Gln151Glu | rs78482768 (https://www.ncbi.nlm.nih.gov/snp/rs78482768)
CYP2D6*28 | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*28 | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*29^[1]^ | 1660G>A+1662G>C | NM_000106.6:c.406G>A + NM_000106.6:c.408G>C | NP_000097.3:p.Val136Met + NP_000097.3:p.Val136= | rs61736512 (https://www.ncbi.nlm.nih.gov/snp/rs61736512) + rs1058164 (https://www.ncbi.nlm.nih.gov/snp/rs1058164)
CYP2D6*29^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*29^[1]^ | 3184G>A | NM_000106.6:c.1012G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/598263/) | NP_000097.3:p.Val338Met | rs59421388 (https://www.ncbi.nlm.nih.gov/snp/rs59421388)
CYP2D6*29^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*31^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D6*31^[2]^ | 4043G>A | NM_000106.6:c.1319G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/183247/) | NP_000097.3:p.Arg440His | rs267608319 (https://www.ncbi.nlm.nih.gov/snp/rs267608319)
CYP2D6*31^[2]^ | 4181G>C | NM_000106.6:c.1457G>C | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*36^[3]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*36^[3]^ | 4129C>G | NM_000106.6:c.1405C>G | NP_000097.3:p.Pro469Ala | rs1135833 (https://www.ncbi.nlm.nih.gov/snp/rs1135833)
CYP2D6*36^[3]^ | 4132A>G | NM_000106.6:c.1408A>G | NP_000097.3:p.Thr470Ala | rs1135835 (https://www.ncbi.nlm.nih.gov/snp/rs1135835)
CYP2D6*36^[3]^ | 4156C>T+4157A>C | NM_000106.6:c.1432C>T+ NM_000106.6:c.1433A>C | NP_000097.3:p.His47Ser | rs28371735 (https://www.ncbi.nlm.nih.gov/snp/rs28371735)+ rs766507177 (https://www.ncbi.nlm.nih.gov/snp/rs766507177)
CYP2D6*36^[3]^ | 4159G>C | NM_000106.6:c.1435G>C | NP_00097.3:p.Gly479Arg
CYP2D6*36^[3]^ | 4165T>G | NM_000106.6:c.1441T>G | NP_00097.3:p.Phe481Val
CYP2D6*36^[3]^ | 4168G>A+4169C>G | NM_000106.6:c.1444G>A+ NM_000106.6:c.1445C>G | NP_000097.3:p.Ala482Ser | rs74478221 (https://www.ncbi.nlm.nih.gov/snp/rs74478221)+ rs75467367 (https://www.ncbi.nlm.nih.gov/snp/rs75467367)
CYP2D6*36^[3]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D4*40^[2]^ | 1022C>T | NM_000106.6:c.320C>T | NP_000097.3:p.Thr107Ile | rs28371706 (https://www.ncbi.nlm.nih.gov/snp/rs28371706)
CYP2D4*40^[2]^ | 1864_1865insTTTCGCCCC[2] | NM_000106.6:c.514TTTCGCCCC[3] | NP_000097.3:p.172FRP[3] | rs72549356 (https://www.ncbi.nlm.nih.gov/snp/rs72549356)
CYP2D4*40^[2]^ | 2851C>T | NM_000106.6:c.886C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/242771/) | NP_000097.3:p.Arg296Cys | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947/)
CYP2D4*40^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*41^[1]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*41^[1]^ | 2989G>A | NM_000106.6:c.985+39G>A (https://www.ncbi.nlm.nih.gov/clinvar/variation/39381/) | Variant occurs in a non-coding region (impacts slicing). | rs28371725 (https://www.ncbi.nlm.nih.gov/snp/rs28371725)
CYP2D6*41^[1]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/830235/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*49^[2]^ | 100C>T | NM_000106.6:c.100C>T (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | NP_000097.3:p.Pro34Ser (https://www.ncbi.nlm.nih.gov/clinvar/variation/16893/) | rs1065852 (https://www.ncbi.nlm.nih.gov/snp/rs1065852)
CYP2D6*49^[2]^ | 1612T>A | NM_00106.6:c.358T>A | NP_000097.3:p.Phe120Ile | rs1135822 (https://www.ncbi.nlm.nih.gov/snp/rs1135822)
CYP2D6*49^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*56^[2]^ | 3202C>T | NM_000106.6:c.1030C>T | NP_000097.3:p.Arg344Ter | rs72549347 (https://www.ncbi.nlm.nih.gov/snp/rs72549347)
CYP2D6*56^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)
CYP2D6*59^[2]^ | 2851C>T | NM_000106.6:c.886T>C (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | NP_000097.3:p.Cys296Arg (http://www.ncbi.nlm.nih.gov/clinvar/variation/16895/) | rs16947 (https://www.ncbi.nlm.nih.gov/snp/rs16947)
CYP2D6*59^[2]^ | 2940G>A | NM_000106.6:c.975G>A | NP_000097.3:p.Pro325= | rs79292917 (https://www.ncbi.nlm.nih.gov/snp/rs79292917)
CYP2D6*59^[2]^ | 4181G>C | NM_000106.6:c.1457G>C (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | NP_000097.3:p.Ser486Thr (https://www.ncbi.nlm.nih.gov/clinvar/variation/242701/) | rs1135840 (https://www.ncbi.nlm.nih.gov/snp/rs1135840)

^[1]^ AMP Tier 1 allele, (82)

^[2]^ AMP Tier 2 allele, (82)

^[3]^ CYP2D6*36 is a gene conversion with CYP2D7; variants provided here are from the Pharmacogene Variation Consortium.

Alleles described in this table are selected based on discussion in the text above. This is not intended to be an exhaustive description of known alleles.

Guidelines for the description and nomenclature of gene variations are available from the Human Genome Variation Society (83).

Nomenclature for Cytochrome P450 enzymes is available from the Pharmacogene Variation (PharmVar (http://www.pharmvar.org/)) Consortium (84).

## Acknowledgments

The author would like to thank Roger S. McIntyre, MD, FRCPC, Professor of Psychiatry and Pharmacology, University of Toronto, Chairman and Executive Director, Brain and Cognition Discovery Foundation (BCDF), Toronto, Ontario, Canada; Natasha Petry, PharmD, MPH, BCACP, Associate Professor, North Dakota State University, Fargo, ND, and Clinical Pharmacist, Sanford Health Imagenetics, Sioux Falls, SD, USA; and Zachary Woodward, PharmD, Commander U.S. Public Health Service, U.S. Coast Guard Base Kodiak, AK, USA for reviewing this summary.

## Version History

Version 1.0 was published on November 13, 2024.

A minor revision (version 1.1) was published on January 17, 2025 to correct a formatting error as well as update the CYP2D6 Allele Nomenclature table with the AMP Tier 1 and Tier 2 allele designations and provide additional citations in the table footer. There are no changed clinical recommendations in this minor revision.

A minor revision (version 1.2) was published on July 28, 2026 to update the resource links to ClinPGx (formerly PharmGKB). There are no changes to clinical or testing recommendations in this revision.

## References

1 INGREZZA- valbenazine capsule, INGREZZA- valbenazine kit, INGREZZA SPRINKLE- valbenazine capsule. San Diego, CA: Inc., N.B.; 2024. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=4c970164-cafb-421f-9eb5-c226ef0a3417.
2 Dysval, Valbenazine tosilate, Review Report [Cited. Available from https://www.pmda.go.jp/files/000252828.pdf.
3 Farber, R.H., A. Angelov, K. Kim, T. Carmack, et al., Clinical development of valbenazine for tics associated with Tourette syndrome. Expert Rev Neurother, 2021. 21(4): p. 393–404.33682568
4 Koch, J., W.X. Shi, and K. Dashtipour, VMAT2 inhibitors for the treatment of hyperkinetic movement disorders. Pharmacol Ther, 2020. 212: p. 107580.32454050
5 Luo, R., H. Bozigian, R. Jimenez, G. Loewen, et al., Single Dose and Repeat Once-Daily Dose Safety, Tolerability and Pharmacokinetics of Valbenazine in Healthy Male Subjects. Psychopharmacol Bull, 2017. 47(3): p. 44–52.28839339
6 Grigoriadis, D.E., E. Smith, S.R.J. Hoare, A. Madan, et al., Pharmacologic Characterization of Valbenazine (NBI-98854) and Its Metabolites. J Pharmacol Exp Ther, 2017. 361(3): p. 454–461.28404690
7 Chung, W.K., I. Hwang, B. Kim, J. Jung, et al., Pharmacokinetics, safety and tolerability of valbenazine in Korean CYP2D6 normal and intermediate metabolizers. Clin Transl Sci, 2023. 16(3): p. 512–523.36514192
8 Zhang, Y., X. Jia, X. Shi, Y. Chen, et al., Mining of neurological adverse events associated with valbenazine: A post-marketing analysis based on FDA adverse event reporting system. Gen Hosp Psychiatry, 2024. 90: p. 22–29.38901166
9 Wong, S., G.H. Le, A.T.H. Kwan, T.G. Rhee, et al., Risk of VMAT2 inhibitors on suicidality and parkinsonism: report utilizing the United States Food and Drug Administration adverse event reporting system. Int Clin Psychopharmacol, 2025. 40(3): p. 176–181.38727416
10 Furr Stimming, E., D.O. Claassen, E. Kayson, J. Goldstein, et al., Safety and efficacy of valbenazine for the treatment of chorea associated with Huntington's disease (KINECT-HD): a phase 3, randomised, double-blind, placebo-controlled trial. Lancet Neurol, 2023. 22(6): p. 494–504.37210099
11 Hauser, R.A., S.A. Factor, S.R. Marder, M.A. Knesevich, et al., KINECT 3: A Phase 3 Randomized, Double-Blind, Placebo-Controlled Trial of Valbenazine for Tardive Dyskinesia. Am J Psychiatry, 2017. 174(5): p. 476–484.28320223
12 Horiguchi, J., K. Watanabe, K. Kondo, A. Iwatake, et al., Efficacy and safety of valbenazine in Japanese patients with tardive dyskinesia: A multicenter, randomized, double-blind, placebo-controlled study (J-KINECT). Psychiatry Clin Neurosci, 2022. 76(11): p. 560–569.36114799
13 Niemann, N. and J. Jankovic, Real-World Experience With VMAT2 Inhibitors. Clin Neuropharmacol, 2019. 42(2): p. 37–41.30870235
14 Akbar, U., D.S. Kim, and J.H. Friedman, Valbenazine-induced parkinsonism. Parkinsonism Relat Disord, 2020. 70: p. 13–14.31785443
15 Vasireddy, R.P., B. Sokola, and Z. Guduru, New generation VMAT2 inhibitors induced parkinsonism. Clin Park Relat Disord, 2020. 3: p. 100078.34316656
16 Valbenazine, in Drugs and Lactation Database (LactMed(R)). 2006: Bethesda (MD). Available from https://www.ncbi.nlm.nih.gov/pubmed/37748010.
17 Patel, N.J. and J. Jankovic, NKX2-1-Related Disorders, in GeneReviews((R)), M.P. Adam, et al., Editors. 1993: Seattle (WA). Available from https://www.ncbi.nlm.nih.gov/pubmed/24555207.
18 Sajatovic, M., G.S. Alexopoulos, J. Burke, K. Farahmand, et al., The effects of valbenazine on tardive dyskinesia in older and younger patients. Int J Geriatr Psychiatry, 2020. 35(1): p. 69–79.31617235
19 Watanabe, Y., Y. Susuta, M. Nagano, H. Masui, et al., Efficacy and Safety of Valbenazine in Elderly and Nonelderly Japanese Patients With Tardive Dyskinesia: A Post Hoc Analysis of the J-KINECT Study. J Clin Psychopharmacol, 2024. 44(6): p. 551–560.39186921
20 Citrome, L., Clinical management of tardive dyskinesia: Five steps to success. J Neurol Sci, 2017. 383: p. 199–204.29246613
21 Raza, M. and J.A. Mars, Tardive Dyskinesia, in StatPearls. 2026: Treasure Island (FL). Available from https://www.ncbi.nlm.nih.gov/pubmed/28846278.
22 Lu, J.Y., A.K. Tiwari, N. Freeman, G.C. Zai, et al., Liver enzyme CYP2D6 gene and tardive dyskinesia. Pharmacogenomics, 2020. 21(15): p. 1065–1072.32969762
23 Citrome, L., Tardive dyskinesia: placing vesicular monoamine transporter type 2 (VMAT2) inhibitors into clinical perspective. Expert Rev Neurother, 2018. 18(4): p. 323–332.29557243
24 Bhidayasiri, R., O. Jitkritsadakul, J.H. Friedman, and S. Fahn, Updating the recommendations for treatment of tardive syndromes: A systematic review of new evidence and practical treatment algorithm. J Neurol Sci, 2018. 389: p. 67–75.29454493
25 Cummings, M.A., G.J. Proctor, and S.M. Stahl, Deuterium Tetrabenazine for Tardive Dyskinesia. Clin Schizophr Relat Psychoses, 2018. 11(4): p. 214–220.29341821
26 Niemann, N. and J. Jankovic, Treatment of Tardive Dyskinesia: A General Overview with Focus on the Vesicular Monoamine Transporter 2 Inhibitors. Drugs, 2018. 78(5): p. 525–541.29484607
27 Scorr, L.M. and S.A. Factor, VMAT2 inhibitors for the treatment of tardive dyskinesia. J Neurol Sci, 2018. 389: p. 43–47.29433808
28 Rakesh, G., A. Muzyk, S.T. Szabo, S. Gupta, et al., Tardive dyskinesia: 21st century may bring new treatments to a forgotten disorder. Ann Clin Psychiatry, 2017. 29(2): p. 108–119.28207919
29 Besag, F.M.C., M.J. Vasey, I. Salim, and C. Hollis, Tardive Dyskinesia with Antipsychotic Medication in Children and Adolescents: A Systematic Literature Review. Drug Saf, 2024. 47(11): p. 1095–1126.38862692
30 Solmi, M., G. Pigato, J.M. Kane, and C.U. Correll, Clinical risk factors for the development of tardive dyskinesia. J Neurol Sci, 2018. 389: p. 21–27.29439776
31 Citrome, L., Reprint of: Clinical management of tardive dyskinesia: Five steps to success. J Neurol Sci, 2018. 389: p. 61–66.29519687
32 Anderson, K.E., D. Stamler, M.D. Davis, S.A. Factor, et al., Deutetrabenazine for treatment of involuntary movements in patients with tardive dyskinesia (AIM-TD): a double-blind, randomised, placebo-controlled, phase 3 trial. Lancet Psychiatry, 2017. 4(8): p. 595–604.28668671
33 Citrome, L., Deutetrabenazine for tardive dyskinesia: A systematic review of the efficacy and safety profile for this newly approved novel medication-What is the number needed to treat, number needed to harm and likelihood to be helped or harmed? Int J Clin Pract, 2017. 71(11).
34 Hauser, R.A. and D. Truong, Tardive dyskinesia: Out of the shadows. J Neurol Sci, 2018. 389: p. 1–3.29449008
35 Fernandez, H.H., S.A. Factor, R.A. Hauser, J. Jimenez-Shahed, et al., Randomized controlled trial of deutetrabenazine for tardive dyskinesia: The ARM-TD study. Neurology, 2017. 88(21): p. 2003–2010.28446646
36 Elsheikh, S.S.M., D.J. Muller, and J.G. Pouget, Pharmacogenetics of Antipsychotic Treatment in Schizophrenia. Methods Mol Biol, 2022. 2547: p. 389–425.36068471
37 Ivanova, S.A., V.A. Toshchakova, M.L. Filipenko, O.Y. Fedorenko, et al., Cytochrome P450 1A2 co-determines neuroleptic load and may diminish tardive dyskinesia by increased inducibility. World J Biol Psychiatry, 2015. 16(3): p. 200–5.25602162
38 Koning, J.P., J. Vehof, H. Burger, B. Wilffert, et al., Association of two DRD2 gene polymorphisms with acute and tardive antipsychotic-induced movement disorders in young Caucasian patients. Psychopharmacology (Berl), 2012. 219(3): p. 727–36.21750899
39 Steen, V.M., R. Lovlie, T. MacEwan, and R.G. McCreadie, Dopamine D3-receptor gene variant and susceptibility to tardive dyskinesia in schizophrenic patients. Mol Psychiatry, 1997. 2(2): p. 139–45.9106238
40 Bakker, P.R., P.N. van Harten, and J. van Os, Antipsychotic-induced tardive dyskinesia and the Ser9Gly polymorphism in the DRD3 gene: a meta analysis. Schizophr Res, 2006. 83(2-3): p. 185–92.16513329
41 Lerer, B., R.H. Segman, E.C. Tan, V.S. Basile, et al., Combined analysis of 635 patients confirms an age-related association of the serotonin 2A receptor gene with tardive dyskinesia and specificity for the non-orofacial subtype. Int J Neuropsychopharmacol, 2005. 8(3): p. 411–25.15857569
42 Zai, C.C., A.K. Tiwari, D.J. Muller, V. De Luca, et al., The catechol-O-methyl-transferase gene in tardive dyskinesia. World J Biol Psychiatry, 2010. 11(6): p. 803–12.20586531
43 Syu, A., H. Ishiguro, T. Inada, Y. Horiuchi, et al., Association of the HSPG2 gene with neuroleptic-induced tardive dyskinesia. Neuropsychopharmacology, 2010. 35(5): p. 1155–64.20072119
44 Greenbaum, L., A. Alkelai, P. Zozulinsky, Y. Kohn, et al., Support for association of HSPG2 with tardive dyskinesia in Caucasian populations. Pharmacogenomics J, 2012. 12(6): p. 513–20.21808285
45 Nofziger, C., A.J. Turner, K. Sangkuhl, M. Whirl-Carrillo, et al., PharmVar GeneFocus: CYP2D6. Clin Pharmacol Ther, 2020. 107(1): p. 154–170.31544239
46 Gaedigk, A., M. Ingelman-Sundberg, N.A. Miller, J.S. Leeder, et al., The Pharmacogene Variation (PharmVar) Consortium: Incorporation of the Human Cytochrome P450 (CYP) Allele Nomenclature Database. Clin Pharmacol Ther, 2018. 103(3): p. 399–401.29134625
47 Caudle, K.E., H.M. Dunnenberger, R.R. Freimuth, J.F. Peterson, et al., Standardizing terms for clinical pharmacogenetic test results: consensus terms from the Clinical Pharmacogenetics Implementation Consortium (CPIC). Genet Med, 2017. 19(2): p. 215–223.27441996
48 CYP2D6 allele functionality table [Cited 6 June 2024]. Available from https://api.clinpgx.org/v1/download/file/attachment/CYP2D6_allele_functionality_reference.xlsx.
49 Yokota, H., S. Tamura, H. Furuya, S. Kimura, et al., Evidence for a new variant CYP2D6 allele CYP2D6J in a Japanese population associated with lower in vivo rates of sparteine metabolism. Pharmacogenetics, 1993. 3(5): p. 256–63.8287064
50 Ingelman-Sundberg, M., Genetic polymorphisms of cytochrome P450 2D6 (CYP2D6): clinical consequences, evolutionary aspects and functional diversity. Pharmacogenomics J, 2005. 5(1): p. 6–13.15492763
51 ClinPGx [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*4 [Cited 26 Sept 2016]. Available from https://www.clinpgx.org/haplotype/PA165816579.
52 ClinPGx [Internet]. Palo Alto (CA): Stanford University. Haplotype CYP2D6*10 [Cited 26 Sept 2016]. Available from https://www.clinpgx.org/haplotype/PA165816582.
53 Bradford, L.D., CYP2D6 allele frequency in European Caucasians, Asians, Africans and their descendants. Pharmacogenomics, 2002. 3(2): p. 229–43.11972444
54 Turner, A.J., C. Nofziger, B.E. Ramey, R.C. Ly, et al., PharmVar Tutorial on CYP2D6 Structural Variation Testing and Recommendations on Reporting. Clin Pharmacol Ther, 2023. 114(6): p. 1220–1237.37669183
55 PharmVar. CYP2D6. 2024 [cited 2024; Available from: https://www.pharmvar.org/gene/CYP2D6.
56 Cicali, E.J., D.M. Smith, B.Q. Duong, L.G. Kovar, et al., A Scoping Review of the Evidence Behind Cytochrome P450 2D6 Isoenzyme Inhibitor Classifications. Clin Pharmacol Ther, 2020. 108(1): p. 116–125.31910286
57 US FDA. Drug Development and Drug Interactions | Table of Substrates, Inhibitors and Inducers. 2023 5 June 2023 7 June 2024]; Available from: https://www.fda.gov/drugs/drug-interactions-labeling/drug-development-and-drug-interactions-table-substrates-inhibitors-and-inducers.
58 Smith, D.M., K.W. Weitzel, A.R. Elsey, T. Langaee, et al., CYP2D6-guided opioid therapy improves pain control in CYP2D6 intermediate and poor metabolizers: a pragmatic clinical trial. Genet Med, 2019. 21(8): p. 1842–1850.30670877
59 Monte, A.A., K. West, K.T. McDaniel, H.K. Flaten, et al., CYP2D6 Genotype Phenotype Discordance Due to Drug-Drug Interaction. Clin Pharmacol Ther, 2018. 104(5): p. 933–939.29882961
60 PRODUCT MONOGRAPH INCLUDING PATIENT MEDICATION INFORMATION, AA-METOPROLOL SR. Vaughan, Ontario, Canada: AA Pharma Inc.; 2022. Available from: https://pdf.hres.ca/dpd_pm/00067786.PDF.
61 Patel, J.N., S.A. Morris, R. Torres, B. Rhead, et al., Pharmacogenomic insights in psychiatric care: uncovering novel actionability, allele-specific CYP2D6 copy number variation, and phenoconversion in 15,000 patients. Mol Psychiatry, 2024. 29(11): p. 3495–3502.38783055
62 den Uil, M.G., H.W. Hut, K.R. Wagelaar, H. Abdullah-Koolmees, et al., Pharmacogenetics and phenoconversion: the influence on side effects experienced by psychiatric patients. Front Genet, 2023. 14: p. 1249164.37693320
63 Cicali, E.J., A.L. Elchynski, K.J. Cook, J.T. Houder, et al., How to Integrate CYP2D6 Phenoconversion Into Clinical Pharmacogenetics: A Tutorial. Clin Pharmacol Ther, 2021. 110(3): p. 677–687.34231197
64 Online Mendelian Inheritance in Man (OMIM). PARKINSONISM-DYSTONIA 2, INFANTILE-ONSET [Cited 1 September 2024]. Available from https://omim.org/entry/618049.
65 Rilstone, J.J., R.A. Alkhater, and B.A. Minassian, Brain dopamine-serotonin vesicular transport disease and its treatment. N Engl J Med, 2013. 368(6): p. 543–50.23363473
66 Jacobsen, J.C., C. Wilson, V. Cunningham, E. Glamuzina, et al., Brain dopamine-serotonin vesicular transport disease presenting as a severe infantile hypotonic parkinsonian disorder. J Inherit Metab Dis, 2016. 39(2): p. 305–8.26497564
67 Rath, M., G.C. Korenke, J. Najm, G.F. Hoffmann, et al., Exome sequencing results in identification and treatment of brain dopamine-serotonin vesicular transport disease. J Neurol Sci, 2017. 379: p. 296–297.28716265
68 Padmakumar, M., J. Jaeken, V. Ramaekers, L. Lagae, et al., A novel missense variant in SLC18A2 causes recessive brain monoamine vesicular transport disease and absent serotonin in platelets. JIMD Rep, 2019. 47(1): p. 9–16.31240161
69 Zhai, H., Y. Zheng, Y. He, Y. Zhang, et al., A case report of infantile parkinsonism-dystonia-2 caused by homozygous mutation in the SLC18A2 gene. Int J Neurosci, 2023. 133(5): p. 574–577.34078222
70 Saida, K., R. Maroofian, T. Sengoku, T. Mitani, et al., Brain monoamine vesicular transport disease caused by homozygous SLC18A2 variants: A study in 42 affected individuals. Genet Med, 2023. 25(1): p. 90–102.36318270
71 Tsai, H.T., S.N. Caroff, D.D. Miller, J. McEvoy, et al., A candidate gene study of Tardive dyskinesia in the CATIE schizophrenia trial. Am J Med Genet B Neuropsychiatr Genet, 2010. 153B(1): p. 336–40.19475583
72 Zai, C.C., A.K. Tiwari, M. Mazzoco, V. de Luca, et al., Association study of the vesicular monoamine transporter gene SLC18A2 with tardive dyskinesia. J Psychiatr Res, 2013. 47(11): p. 1760–5.24018103
73 Burman, J., C.H. Tran, C. Glatt, N.B. Freimer, et al., The effect of rare human sequence variants on the function of vesicular monoamine transporter 2. Pharmacogenetics, 2004. 14(9): p. 587–94.15475732
74 Smith, E., G. Loewen, R. Luo, S. Ingersoll, et al., Effect of Paroxetine on the Pharmacokinetics of Valbenazine and its Active Metabolite (9). Neurology, 2020. 94(15_supplement).
75 Nagano, M., Y. Susuta, H. Masui, Y. Watanabe, et al., Efficacy and Safety of Valbenazine in Japanese Patients With Tardive Dyskinesia and Schizophrenia/Schizoaffective Disorder or Bipolar Disorder/Depressive Disorder: Primary Results and Post Hoc Analyses of the J-KINECT Study. J Clin Psychopharmacol, 2024. 44(2): p. 107–116.38421921
76 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and the European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021. 23(9): p. 1047–1064.34118403
77 Hicks, J.K., J.R. Bishop, K. Sangkuhl, D.J. Muller, et al., Clinical Pharmacogenetics Implementation Consortium (CPIC) Guideline for CYP2D6 and CYP2C19 Genotypes and Dosing of Selective Serotonin Reuptake Inhibitors. Clin Pharmacol Ther, 2015. 98(2): p. 127–34.25974703
78 O'Shea, J., M. Ledwidge, J. Gallagher, C. Keenan, et al., Pharmacogenetic interventions to improve outcomes in patients with multimorbidity or prescribed polypharmacy: a systematic review. Pharmacogenomics J, 2022. 22(2): p. 89–99.35194175
79 Hayashi, M., D.A. Hamdy, and S.H. Mahmoud, Applications for pharmacogenomics in pharmacy practice: A scoping review. Res Social Adm Pharm, 2022. 18(7): p. 3094–3118.34474980
80 Swen, J.J., C.H. van der Wouden, L.E. Manson, H. Abdullah-Koolmees, et al., A 12-gene pharmacogenetic panel to prevent adverse drug reactions: an open-label, multicentre, controlled, cluster-randomised crossover implementation study. Lancet, 2023. 401(10374): p. 347–356.36739136
81 Hjemas, B.J., K. Bovre, K. Bjerknes, L. Mathiesen, et al., Implementation of pharmacogenetic testing in medication reviews in a hospital setting. Br J Clin Pharmacol, 2023. 89(10): p. 3116–3125.37277227
82 Pratt, V.M., L.H. Cavallari, A.L. Del Tredici, A. Gaedigk, et al., Recommendations for Clinical CYP2D6 Genotyping Allele Selection: A Joint Consensus Recommendation of the Association for Molecular Pathology, College of American Pathologists, Dutch Pharmacogenetics Working Group of the Royal Dutch Pharmacists Association, and European Society for Pharmacogenomics and Personalized Therapy. J Mol Diagn, 2021.
83 den Dunnen, J.T., R. Dalgleish, D.R. Maglott, R.K. Hart, et al., HGVS Recommendations for the Description of Sequence Variants: 2016 Update. Hum Mutat, 2016. 37(6): p. 564–9.26931183
84 Gaedigk, A., S.T. Casey, M. Whirl-Carrillo, N.A. Miller, et al., Pharmacogene Variation Consortium: A Global Resource and Repository for Pharmacogene Variation. Clin Pharmacol Ther, 2021. 110(3): p. 542–545.34091888

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug. Certain terms, genes and genetic variants may be corrected in accordance with nomenclature standards, where necessary. We have given the full name of abbreviations, shown in square brackets, where necessary.