# Trastuzumab Therapy and ERBB2 Genotype

## Introduction

Trastuzumab (brand name, Herceptin) is a monoclonal antibody used in the treatment of breast and gastric/gastroesophageal cancer. It targets an epidermal growth factor receptor encoded by the ERBB2 gene, which is commonly referred to as the HER2 gene. Multiple biosimilar products to Herceptin are now available: Kanjinti, Trazimera, Ontruzant, Herzuma and Ogivri.

The ERBB2 gene is overexpressed in 15–20% of breast cancers and 15–20% of gastric and esophageal cancers. Overall, “HER2 positive” tumors are associated with a faster rate of growth and—in some cases—a poorer prognosis in absence of anti-HER2 therapy. The use of trastuzumab in treatment regimens improves outcomes, with limited adverse effects that include cardiac toxicity.

The FDA-approved drug label states that trastuzumab should only be used to treat individuals with tumors that have either HER2 protein overexpression or ERBB2 gene amplification, as determined by an accurate and validated FDA-approved assay, specific for the type of tumor tested (breast or gastric) (Table 1)(1). The FDA-approved drug label for all trastuzumab biosimilars describes only the use of trastuzumab in adjuvant treatment of breast cancer, though its efficacy in neoadjuvant care for breast cancer (reviewed in part by (2)) and esophageal adenocarcinoma (3) has also been documented.

The most recent update (2018) of the American Society of Clinical Oncology (ASCO)/College of American Pathologists (CAP) guidelines continues to state that all newly diagnosed individuals with breast cancer must have an HER2 test performed. Individuals who then develop metastatic disease must have an HER2 test performed in a metastatic site, if tissue sample is available (4).

Table 1.

The FDA Indications and Usage of Trastuzumab (2020)

Individual selection* | Breast cancer (adjuvant treatment) | Metastatic breast cancer | Metastatic gastric cancer
Tumor HER2 status | HER2-positive | HER2-positive | HER2-positive
Indications and usage | Indicated for adjuvant treatment of HER2 overexpressing node positive or node negative breast cancer. -As part of a treatment regimen consisting of doxorubicin, cyclophosphamide, and either paclitaxel or docetaxel ^#^ -As part of a treatment regimen with docetaxel and carboplatin ^#^ -As a single agent following multi-modality anthracycline based therapy ^#^ | Indicated in combination with paclitaxel for first-line treatment of HER2-overexpressing metastatic breast cancer, or as a single agent for treatment of HER2-overexpressing breast cancer | Indicated for the treatment of individuals with HER2-overexpressing metastatic gastric or gastroesophageal junction adenocarcinoma who have not received prior treatment for metastatic disease. (in combination with cisplatin and capecitabine or 5-fluorouracil)^#^

* Select individuals based on HER2 protein overexpression or ERBB2 gene amplification in tumor specimens.

# Combination therapy administration notes are specific to FDA labels for Trazimera and Ogivri (5, 6)

This FDA table was adapted from (1).

## Drug Class: HER2 Inhibitors

Human epidermal growth factor receptor 2 (commonly referred to as HER2 or HER-2/neu) is encoded by the gene ERBB2, which is a transmembrane receptor tyrosine kinase. Overexpression of ERBB2 leads to rapid cell growth in multiple types of solid tumors. The HER2 can be inactivated by a class of chemicals known as tyrosine kinase inhibitors or via targeted monoclonal antibodies. An increasing number of HER2-targeted therapies have been approved to treat HER2-positive breast cancer, including:

- Pertuzumab––monoclonal antibody (brand name Perjeta)
- Trastuzumab––monoclonal antibody (brand name Herceptin)
- Ado-trastuzumab emtansine––antibody-drug-conjugate (monoclonal antibody attached to a chemotherapy drug (brand name Kadcyla, also called TDM-1)
- Fam-trastuzumab deruxtecan––antibody-drug-conjugate (brand name Enhertu)
- Neratinib––a kinase inhibitor (brand name Nerlynx)
- Lapatinib––a kinase inhibitor (brand name Tykerb)
- Tucatinib––a kinase inhibitor (brand name Tykysa)
- Dacomitinib––a kinase inhibitor (brand name Vizimpro)

There are several more anti-HER2 drugs progressing through clinical trials, and some trials are looking at whether HER2-targeted therapies could be used to treat other tumors that overexpress HER2, such as colorectal and non-small-cell lung cancer. However, early results are not replicating the success of HER2-targeted therapies in breast and gastric cancer (7, 8, 9).

## Drug: Trastuzumab

Trastuzumab (brand name, Herceptin) is a monoclonal antibody that targets HER2 (a tyrosine kinase receptor, encoded by the gene ERBB2). Multiple biosimilar products to trastuzumab are now available under the brand names Kanjinti, Trazimera, Ontruzant, Herzuma and Ogivri. Trastuzumab is only used to treat specific tumors that overexpress ERBB2, which are known as “HER2-positive” tumors.

Trastuzumab is the first molecular targeted agent approved as standard therapy for gastric cancer, and is the only HER2 targeted therapy approved for the treatment of advanced gastric cancer. The 2015 NCCN guidelines recommend the first-line treatment of trastuzumab combined with chemotherapy in individuals overexpressing HER2 (10).

Trastuzumab was also the first targeted anti-HER2 therapy available for metastatic HER2-positive breast cancer, and led to significant improvement in prognosis over the previous standard of care chemotherapy regimens, and was the first monoclonal antibody to be approved for non-metastatic HER2-positive breast cancer (11).

Trastuzumab is typically used with chemotherapy as neoadjuvant or adjuvant treatment of early-stage HER2-positive breast cancer. Neoadjuvant therapy is given before primary therapy to shrink a tumor to an operable size, help make decisions for further therapy after surgery, allow for breast-conserving surgery, and increase the chance of long-term, disease-free survival. Adjuvant therapies are used after surgery to increase the chance of long-term disease-free survival. Trastuzumab can be used with chemotherapy with or without another HER2 targeted agent pertuzumab (12). Trastuzumab is also used in the treatment of HER2-positive metastatic breast cancer and HER2-positive metastatic gastric cancer (1, 13).

Pertuzumab, another targeted anti-HER2 therapy, can also be added to multiple treatment regimens, including trastuzumab/chemotherapy combination therapy, in the neoadjuvant, adjuvant, or metastatic setting (14, 15, 16, 17, 18). Regardless of whether initial treatment was given before or after surgery, adjuvant trastuzumab should be continued to complete one year of therapy.

Recently, another HER2-targeted therapy ado-trastuzumab emtansine (Kadcyla) has been approved by the FDA for adjuvant treatment of HER2-positive early breast cancer (EBC) in individuals who have residual invasive disease after receiving taxane and trastuzumab-based treatment.

Before treatment with trastuzumab begins, overexpression of the ERBB2 protein or amplification of the ERBB2 gene must first be determined. The FDA recommends that testing be performed using an FDA-approved test for the specific tumor type (breast or gastric tumor), in a laboratory with demonstrated proficiency with the technology being used. This is because the benefits of trastuzumab have only been proven in individuals with tumors that overexpress ERBB2. In addition, although trastuzumab is generally well tolerated, the risks of treatment include infusion reactions, pulmonary toxicity, and cardiomyopathy that can result in cardiac failure (1, 19).

Trastuzumab targets the ERBB2 receptor protein by binding to the juxtamembrane portion of the extracellular domain. This binding limits the receptor’s ability to activate its intrinsic tyrosine kinase, which in turn, limits the activation of numerous signaling pathways that can promote the growth of cancerous cells.

A number of proposed mechanisms may underlie the anti-tumor effects of trastuzumab. Of note, when HER2 is overexpressed, HER2 receptors exist on the cell surface as homodimers and heterodimers with other HER family receptors. It has been suggested that trastuzumab has preferential activity against breast cancers driven by HER2 homodimers (20). Additionally, it has been proposed that trastuzumab disrupts signaling activation by the ligand-independent HER2/HER3 complex (21). The HER2-HER3 dimerized receptor is thought to be highly active, triggering many signaling cascades in the absence of a “true” ligand (22).

Another proposed mechanism is antibody-dependent cellular cytotoxicity (ADCC). Once trastuzumab has bound to a cancer cell, immune cells (typically activated natural killer cells) bind to trastuzumab and initiate lysis of the cancer cell (23). Trastuzumab may also mediate the enhanced internalization and degradation of the HER2 receptor, inhibit angiogenesis, and inhibit HER2 shedding by preventing the cleavage of HER2 and the subsequent release of its extracellular domain (24, 25).

Unfortunately, cancer is a complex disease involving many different genes and pathways. Breast cancer or gastric cancer may start to progress again during trastuzumab therapy. Possible mechanisms that may facilitate disease progression during treatment include increased signaling from the HER family of receptors, an upregulation of downstream signaling pathways, and an increased level of insulin growth factor-1 receptor (26, 27, 28, 29, 30, 31).

## Gene: ERBB2 (HER2)

The HER protein family consists of 4 members: the epidermal growth factor receptor (EGFR), ERBB2 (HER2), ERBB3 (HER3), and ERBB4 (HER4) (see Nomenclature for Selected Genes below). All 4 members are transmembrane tyrosine kinase receptors, and they regulate a number of important cellular processes, such as cell growth, survival, and differentiation (32).

The genes ERBB2 and EGFR are proto-oncogenes. Proto-oncogenes are a group of genes that, when mutated or expressed at abnormally high levels, can contribute to normal cells becoming cancerous cells. The mutated version of the proto-oncogene is called an oncogene. Proto-oncogenes typically encode proteins that stimulate cell division, regulate cell differentiation, and halt cell death. All these are important biological processes. However, the increased production of these proteins, caused by oncogenes, can lead to the proliferation of poorly differentiated cancer cells (33).

The official gene symbol for HER2 is ERBB2, which is derived from a viral oncogene with which the receptor shares homology; “v-erb-b2 avian erythroblastic leukemia viral oncogene homolog 2.” However, clinicians commonly refer to the ERBB2 gene as “HER2” or “HER2/neu” (neu was the name given to the gene that caused cancer derived from a rodent neuro/glioblastoma). The HER2 is the legacy gene symbol for ERBB2 and may be more commonly used by the community; HER2 is also commonly used to describe the protein encoded by the ERBB2 gene.

One unique feature of HER2 compared with the other receptors in the HER family is the absence of a known ligand. It is therefore thought that this receptor may permanently be in an activated state, or it may become activated during heterodimerization with one of the other members of the HER family (25, 30). One unique feature of HER3 is that it has very little enzymatic activity compared with the other tyrosine kinase receptors in the HER family. It is therefore thought that an important role of HER3 is to act as a heterodimerization partner for HER2 (34) and other HER family members.

When a partner such as HER3 binds to HER2, the heterodimer undergoes activation, which stimulates the intrinsic tyrosine kinase activity of the receptor. Autophosphorylation of several key residues of the receptor triggers the downstream activation of many commonly used growth factor signaling pathways, such as the PI3K/AKT/mTOR pathway and the RAS/RAF/MEK/ERK pathway (35, 36). Impaired ERBB2 signaling is associated with the development of neurodegenerative diseases (37), such as Alzheimer disease (38), whereas excessive ERBB2 signaling is associated with the development of cancers (39).

The ERBB2 is overexpressed in approximately 15–20% of breast tumors as a result of amplification of the ERBB2 gene, and tumors with increased HER2 typically have a higher growth rate and more aggressive clinical behavior, with the exception of esophagogastric adenocarcinoma (40, 41, 42, 43, 44). Although gene amplification is frequently seen in cancer and other degenerative disorders, the underlying basis for amplification remains largely unknown (45). And in the case of ERBB2, although sequence variants have been identified, it is most commonly a wildtype ERBB2 gene copy that is overexpressed in tumors (46). In approximately 1% of breast cancers, activating mutations in ERBB2 can be identified that are likely to drive tumorigenesis without ERBB2 amplification (47). Importantly, it has recently been shown that these variants are further acquired in estrogen receptor-positive metastatic breast cancer, conferring resistance to endocrine therapy (48). Early results from one study (NCT02564900 (http://clinicaltrials.gov/show/NCT02564900)) suggest that trastuzumab deruxtecan may be effective as an anti-HER2 therapy in HER2-low expressing (HER2 “negative” scores of 1+ or 2+ by standard IHC testing) tumors (49).

## Linking Gene Overexpression with Treatment Response

Overexpression of HER2 is strongly linked to a beneficial treatment response to trastuzumab. As a consequence, current guidelines for breast cancer treatment limit the use of HER2-blocking agents to tumors with HER2 gene amplification or with HER2 protein overexpression (namely, IHC 3+) (4, 42, 43).

### Genetic Testing

The NIH Genetic Testing Registry (GTR) displays tests that are available for the ERBB2 gene (https://www.ncbi.nlm.nih.gov/gtr/all/tests/?term=2064%5bgeneid%5d) and the trastuzumab drug response (https://www.ncbi.nlm.nih.gov/gtr/all/conditions/?term=CN078025). Increased awareness of ERBB2 testing and trastuzumab administration may improve quality of care and individual outcomes (50). In addition, because HER2 expression can change over time in breast cancer, retesting the HER2 status upon change in disease status is helpful in determining the appropriate treatment. Somatic alterations in ERBB2 have been observed in multiple solid tumor types, though the frequency of variants and the specific variants are highly variable (9). Testing of the tumor tissue itself for ERBB2 overexpression is recommended before initiating anti-HER2 therapies.

### Tumor Testing for ERBB2 (HER2) Gene and Protein

There are 2 main methods used for ERBB2/HER2 testing: testing for overexpression of the HER2 protein using immunohistochemistry (IHC) or testing for gene amplification using in situ hybridization (ISH). Each assay type has diagnostic pitfalls that must be avoided, and so the pathologist who reviews the histologic findings should determine the optimal assay (IHC or ISH) for the determination of HER2 status (42, 43).

In an IHC assay, a slice of tumor tissue is stained, along with a control sample that contains high levels of HER2. The tumor sample is then examined by light microscopy to assess the intensity of membrane staining—the amount of staining correlates with the quantity of HER2 protein and is typically graded from 0 to 3+ in breast tumor biopsies (4):

- IHC 0 means no visible staining or membrane staining that is incomplete and is faint/barely perceptible and in ≤ 10% of tumor cells

• IHC 1+ is also an “HER2 negative” result—there is a staining pattern of incomplete membrane staining that is faint/barely perceptible and in >10% of tumor cells

• IHC 2+ is an “HER2 equivocal result”—invasive breast cancer with ‘‘weak to moderate complete membrane staining observed in >10% of tumor cells.’’

• IHC 3+ is an “HER2 positive result”—there is a staining pattern with circumferential membrane staining that is complete, intense and in >10% of tumor cells. This should be readily appreciated using a low-power objective and observed within a homogenous and continuous invasive cell population.

For gastroesophageal adenocarcinoma, a similar scoring metric is used for HER2 testing (51):

- IHC 0 is a negative result, Surgical specimens have no reactivity or membranous activity in <10% of tumor cells; biopsy specimens have no reactivity in any tumor cell
- IHC 1+ is also negative. Surgical specimens have faint/barely perceptible membranous reactivity in ≥10% of tumor cells, cells are reactive in only part of their membrane; biopsy specimens show that tumor cells cluster with faint or barely perceptible membranous reactivity irrespective of percentage of tumor cells stained.
- IHC2+ is “HER2 equivocal”. Surgical specimens have weak to moderate complete, basolateral or lateral membranous reactivity in ≥10% of tumor cells. Biopsy specimens have tumor cells that cluster with weak to moderate complete, basolateral or lateral membranous activity irrespective of percentage of tumor cells stained.
- IHC3+ is HER2 positive. Surgical specimens have Strong complete, basolateral or lateral membranous reactivity in ≥10% of tumor cells. Biopsy specimens show tumor cell cluster* with strong complete, basolateral or lateral membranous activity irrespective of percentage of tumor cells stained

For an equivocal (IHC 2+) result in either breast or gastric cancer, either a reflex test must be ordered (same specimen using ISH), or a new test must be ordered (using a new specimen, if available, using ISH or FISH) to confirm the results.

The ISH assay, or FISH/CISH assay (fluorescence or chromogenic in situ hybridization), measures ERBB2 gene amplification by measuring ERBB2 DNA—the actual number of copies of the ERBB2 genes are counted. Using the FISH assay, under the microscope, the genes appear as red signals or dots, in a blue-stained cancer cell nucleus. The result is usually either FISH negative (normal level of ERBB2 gene) or FISH positive (at least twice as much as normal level of ERBB2 gene), but in a small number of cases the FISH result will be equivocal due to a low level of ERBB2 amplification. The use of a control helps distinguish between a negative result and a non-informative result caused by an error. Approximately 25% of individuals who have an IHC 2+ result will have a FISH positive result (52).

For the complete algorithms for evaluation of HER2 protein expression using IHC or ISH, please see the American Society of Clinical Oncology (ASCO) / College of American Pathologists (CAP) clinical practice guideline update, located here ( 4 , 43 , 51 ).

## Therapeutic Recommendations based on Genotype

This section contains excerpted^1^ information on gene-based dosing recommendations. Neither this section nor other parts of this review contain the complete recommendations from the sources.

### 2020 Statement from the US Food and Drug Administration (FDA)

Select individuals based on HER2 protein overexpression or HER2 gene amplification in tumor specimens. Assessment of HER2 protein overexpression and HER2 gene amplification should be performed using FDA-approved tests specific for breast or gastric cancers by laboratories with demonstrated proficiency. Information on the FDA-approved tests for the detection of HER2 protein overexpression and HER2 gene amplification is available at: http://www.fda.gov/CompanionDiagnostics.

Assessment of HER2 protein overexpression and HER2 gene amplification in metastatic gastric cancer should be performed using FDA-approved tests specifically for gastric cancers due to differences in gastric vs. breast histopathology, including incomplete membrane staining and more frequent heterogeneous expression of HER2 seen in gastric cancers.

Improper assay performance, including use of suboptimally fixed tissue, failure to utilize specified reagents, deviation from specific assay instructions, and failure to include appropriate controls for assay validation, can lead to unreliable results.

Please review the complete therapeutic recommendations that are located here: (1)

FDA-approved medical devices for HER2 can be searched for here (http://www.accessdata.fda.gov/scripts/cdrh/devicesatfda/index.cfm?start_search=1&search_term=HER2).

### 2018 Update: American Society of Clinical Oncology (ASCO) /College of American Pathologists (CAP) Recommendations for Breast Cancer

First released in 2007 and updated in 2013 and 2018, the recommendations by the American Society of Clinical Oncology (ASCO)/College of American Pathologists (CAP) human epidermal growth factor receptor 2 (HER2) testing Expert Panel are aimed at improving the analytic validity of HER2 testing and the clinical utility of HER2 as a predictive biomarker for potential responsiveness to therapies targeting the HER2 protein.

2013: ASCO/CAP Key Recommendations for Oncologists

• Must request HER2 testing on every primary invasive breast cancer (and on metastatic site, if stage IV and if specimen available) from an individual with breast cancer to guide decision to pursue HER2-targeted therapy. This should be especially considered for an individual who previously tested HER2 negative in a primary tumor and presents with disease recurrence with clinical behavior suggestive of HER2-positive or triple-negative disease.

• Should recommend HER2-targeted therapy if HER2 test result is positive, if there is no apparent histopathologic discordance with HER2 testing and if clinically appropriate.

• Must delay decision to recommend HER2-targeted therapy if initial HER2 test result is equivocal. Reflex testing should be performed on the same specimen using the alternative test if initial HER2 test result is equivocal or on an alternative specimen.

• Must not recommend HER2-targeted therapy if HER2 test result is negative and if there is no apparent histopathologic discordance with HER2 testing.

• Should delay decision to recommend HER2-targeted therapy if HER2 status cannot be confirmed as positive or negative after separate HER2 tests (HER2 test result or results equivocal). The oncologist should confer with the pathologist regarding the need for additional HER2 testing on the same or another tumor specimen.

• If the HER2 test result is ultimately deemed to be equivocal, even after reflex testing with an alternative assay (i.e., if neither test is unequivocally positive), the oncologist may consider HER2-targeted therapy. The oncologist should also consider the feasibility of testing another tumor specimen to attempt to definitely establish the tumor HER2 status and guide therapeutic decisions. A clinical decision to ultimately consider HER2-targeted therapy in such cases should be individualized on the basis of individual status (comorbidities, prognosis, and so on) and individual preferences after discussing available clinical evidence.

2018: ASCO/CAP Updated Key Recommendations for HER2 testing

[…]

Two recommendations addressed via correspondence in 2015 are included. First, immunohistochemistry (IHC) 2+ is defined as invasive breast cancer with weak to moderate complete membrane staining observed in >10% of tumor cells. Second, if the initial HER2 test result in a core needle biopsy specimen of a primary breast cancer is negative, a new HER2 test may (not "must") be ordered on the excision specimen based on specific clinical criteria.

Please review the complete ASCO/CAP recommendations in the 2013 update ( 22 ) and 2018 update ( 4 ).

### 2016 American Society of Clinical Oncology (ASCO) /College of American Pathologists (CAP) Recommendations for Gastroesophageal Adenocarcinoma (GEA)

Key Points and Recommendations for Clinicians

- Recommendation 1.1: In individuals with advanced GEA who are potential candidates for HER2-targeted therapy, the treating clinician should request HER2 testing on tumor tissue (Type: evidence based; Quality of evidence: high; Strength of recommendation: strong).
- Recommendation 1.2: Treating clinicians or pathologists should request HER2 testing on tumor tissue in the biopsy or resection specimens (primary or metastasis) preferably prior to the initiation of trastuzumab therapy if such specimens are available and adequate. HER2 testing on FNA specimens (cell blocks) is an acceptable alternative (Type: evidence based; Quality of evidence: moderate/intermediate; Strength of recommendation: recommendation/moderate).
- Recommendation 1.3: Treating clinicians should offer combination chemotherapy and HER2-targeted therapy as the initial treatment for appropriate individuals with HER2 positive tumors who have advanced GEA (Type: evidence based; Quality of evidence: moderate/intermediate; Strength of recommendation: strong).

Key Points and Recommendations for Pathologists

- Recommendation 2.1: Laboratories/pathologists must specify the antibodies and probes used for the test and ensure that assays are appropriately validated for HER2 IHC and ISH on GEA specimens (Type: evidence based; Quality of evidence: moderate/intermediate; Strength of recommendation: strong).
- Recommendation 2.2: When GEA HER2 status is being evaluated, laboratories/pathologists should perform/order IHC testing first, followed by ISH when IHC result is 2+ (equivocal). Positive (3+) or negative (0 or 1+) HER2 IHC results do not require further ISH testing (Type: evidence based; Quality of evidence: high; Strength of recommendation: strong).
- Recommendation 2.3: Pathologists should use the Ruschoff/Hofmann method in scoring HER2 IHC and ISH results for GEA (Type: evidence based; Quality of evidence: moderate/intermediate; Strength of recommendation: strong).
- Recommendation 2.4: Pathologists should select the tissue block with the areas of lowest grade tumor morphology in biopsy and resection specimens. More than one tissue block may be selected if different morphologic patterns are present (Type: evidence based; Quality of evidence: moderate/intermediate; Strength of recommendation: recommendation/moderate).
- Recommendation 2.5: Laboratories should report HER2 test results in GEA specimens in accordance with the CAP “Template for Reporting Results of HER2 (ERBB2) Biomarker Testing of Specimens From Individuals With Adenocarcinoma of the Stomach or Esophagogastric Junction” (Type: evidence based; Quality of evidence: moderate/intermediate; Strength of recommendation: strong).
- Recommendation 2.6: Pathologists should identify areas of invasive adenocarcinoma and also mark areas with strongest intensity of HER2 expression by IHC in GEA specimen for subsequent ISH scoring when required (Type: evidence based; Quality of evidence: moderate/intermediate; Strength of recommendation: strong).
- Recommendation 2.7: Laboratories must incorporate GEA HER2 testing methods into their overall laboratory quality improvement program, establishing appropriate quality improvement monitors as needed to ensure consistent performance in all steps of the testing and reporting process. In particular, laboratories performing GEA HER2 testing should participate in a formal proficiency testing program, if available, or an alternative proficiency assurance activity (Type: evidence based; Quality of evidence: moderate/intermediate; Strength of recommendation: strong).
- Recommendation 2.8: There is insufficient evidence to recommend for or against genomic testing in GEA individuals at this time.

Please review the complete ASCO/CAP recommendations here ( 51 ).

## Nomenclature for Selected Genes Associated with Trastuzumab Response

Official gene symbol | Alternative gene symbols
EGFR | ERBB1 ERBB HER1
ERBB2 | HER2 HER-2 HER-2/neu NEU
ERBB3 | HER3
ERBB4 | HER4

## Acknowledgments

The author would like to thank Priyanka Sharma, MD, Professor of Medicine and Co-Program Leader Drug Discovery, Delivery and Experimental Therapeutics Program, University of Kansas Medical Center, Westwood, KS, USA, Hanneke W.M. van Laarhoven, MD, PhD, PhD, Head of the Department of Medical Oncology, Cancer Center Amsterdam, Amsterdam University Medical Centers, University of Amsterdam, Amsterdam, the Netherlands, Rachel Schiff, PhD, Associate Professor, Breast Center, Baylor College of Medicine, Houston, TX, USA, and Mothaffar Fahed Rimawi, MD, Executive Medical Director & Associate Director of Clinical Affairs, Dan L Duncan Comprehensive Cancer Center, Baylor College of Medicine, Houston, TX, USA for reviewing this summary.

Reviewers for 2015 edition:

The author would like to thank the following individuals for reviewing this summary:

Clifford Hudis, Chief, Breast Medicine Service, Vice President for Government Relations and Chief Advocacy Officer at Memorial Sloan Kettering Cancer Center, and Professor of Medicine, Weill Cornell Medical College, New York, NY, USA

David G. Hicks, Director of Surgical Pathology and Professor of Pathology and Laboratory Medicine at the University of Rochester Medical Center, Rochester, NY, USA

Stanley Lipkowitz, Chief of the Women’s Malignancies Branch, National Cancer Institute, National Institutes of Health, Bethesda, MD, USA

Tracy G. Lively, Deputy Associate Director of the Cancer Diagnosis Program, National Cancer Institute, National Institutes of Health, Bethesda, MD, USA

## Version History

The first edition of this summary, published August 5^th^, 2015 is available here.

The second edition of this summary (v. 2) was published on January 5, 2021.

A minor revision (v. 2.1) was made on May 18, 2026 to update links to cited FDA resources.

A minor revision (v. 2.2) was made on July 6, 2026 to remove a redundant and retired citation to an overview publication regarding HER2/HER3 interaction.

## References

1 ONTRUZANT- trastuzumab injection, powder, lyophilized, for solution ONTRUZANT- ontruzant [package insert]. New Jersey, USA: Corp., M.S.D.; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=a8d34591-b709-492b-84e3-d7764db9366a.
2 Hensing, W., C.A. Santa-Maria, L.L. Peterson, and J.Y. Sheng, Landmark trials in the medical oncology management of early stage breast cancer. Semin Oncol, 2020. 47(5): p. 278–292.32933761
3 Stroes, C.I., S. Schokker, A. Creemers, R.J. Molenaar, et al., Phase II Feasibility and Biomarker Study of Neoadjuvant Trastuzumab and Pertuzumab With Chemoradiotherapy for Resectable Human Epidermal Growth Factor Receptor 2-Positive Esophageal Adenocarcinoma: TRAP Study. J Clin Oncol, 2020. 38(5): p. 462–471.31809243
4 Wolff, A.C., M.E.H. Hammond, K.H. Allison, B.E. Harvey, et al., Human Epidermal Growth Factor Receptor 2 Testing in Breast Cancer: American Society of Clinical Oncology/College of American Pathologists Clinical Practice Guideline Focused Update. J Clin Oncol, 2018. 36(20): p. 2105–2122.29846122
5 TRAZIMERA-QYYP- trastuzumab [package insert]. New York, NY, USA: Pfizer Laboratories Div Pfizer Inc.; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=b9c5e894-27d2-4245-a653-df986fed3c56.
6 OGIVRI- tras tuzumab [package insert]. Rockford, IL, USA: Mylan Institutional LLC; 2020. Available from: https://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=6b7938e6-14c7-4a65-9605-967542ecfb8f.
7 Pernas, S. and S.M. Tolaney, HER2-positive breast cancer: new therapeutic frontiers and overcoming resistance. Ther Adv Med Oncol, 2019. 11: p. 1758835919833519.30911337
8 Wang, J. and B. Xu, Targeted therapeutic options and future perspectives for HER2-positive breast cancer. Signal Transduct Target Ther, 2019. 4: p. 34.31637013
9 Oh, D.Y. and Y.J. Bang, HER2-targeted therapies - a role beyond breast cancer. Nat Rev Clin Oncol, 2020. 17(1): p. 33–48.31548601
10 Bonelli, P., A. Borrelli, F.M. Tuccillo, L. Silvestro, et al., Precision medicine in gastric cancer. World J Gastrointest Oncol, 2019. 11(10): p. 804–829.31662821
11 Kreutzfeldt, J., B. Rozeboom, N. Dey, and P. De, The trastuzumab era: current and upcoming targeted HER2+ breast cancer therapies. Am J Cancer Res, 2020. 10(4): p. 1045–1067.32368385
12 FDA grants regular approval to pertuzumab for adjuvant treatment of HER2-positive breast cancer. 2017 May 18, 2026]; Available from: https://wayback.archive-it.org/7993/20201222065837/https://www.fda.gov/drugs/resources-information-approved-drugs/fda-grants-regular-approval-pertuzumab-adjuvant-treatment-her2-positive-breast-cancer.
13 UpToDate: Treatment protocols for breast cancer [Cited. Available from https://www.uptodate.com/contents/treatment-protocols-for-breast-cancer.
14 PERJETA- pertuzumab injection, solution, concentrate [package insert]. Genetech, I.; 2013. Available from: http://dailymed.nlm.nih.gov/dailymed/drugInfo.cfm?setid=17f85d17-ab71-4f5b-9fe3-0b8c822f69ff.
15 Gianni, L., T. Pienkowski, Y.H. Im, L. Roman, et al., Efficacy and safety of neoadjuvant pertuzumab and trastuzumab in women with locally advanced, inflammatory, or early HER2-positive breast cancer (NeoSphere): a randomised multicentre, open-label, phase 2 trial. Lancet Oncol, 2012. 13(1): p. 25–32.22153890
16 FDA approves ado-trastuzumab emtansine for early breast cancer. FDA May 18, 2026]; Available from: https://wayback.archive-it.org/7993/20201222064213/https://www.fda.gov/drugs/resources-information-approved-drugs/fda-approves-ado-trastuzumab-emtansine-early-breast-cancer.
17 Amiri-Kordestani, L., S. Wedam, L. Zhang, S. Tang, et al., First FDA approval of neoadjuvant therapy for breast cancer: pertuzumab for the treatment of patients with HER2-positive breast cancer. Clin Cancer Res, 2014. 20(21): p. 5359–64.25204553
18 Swain, S.M., D. Miles, S.B. Kim, Y.H. Im, et al., Pertuzumab, trastuzumab, and docetaxel for HER2-positive metastatic breast cancer (CLEOPATRA): end-of-study results from a double-blind, randomised, placebo-controlled, phase 3 study. Lancet Oncol, 2020. 21(4): p. 519–530.32171426
19 Yu, A.F., J.R. Flynn, C.S. Moskowitz, J.M. Scott, et al., Long-term Cardiopulmonary Consequences of Treatment-Induced Cardiotoxicity in Survivors of ERBB2-Positive Breast Cancer. JAMA Cardiol, 2020. 5(3): p. 309–317.31939997
20 Ghosh, R., A. Narasanna, S.E. Wang, S. Liu, et al., Trastuzumab has preferential activity against breast cancers driven by HER2 homodimers. Cancer Res, 2011. 71(5): p. 1871–82.21324925
21 Junttila, T.T., R.W. Akita, K. Parsons, C. Fields, et al., Ligand-independent HER2/HER3/PI3K complex is disrupted by trastuzumab and is effectively inhibited by the PI3K inhibitor GDC-0941. Cancer Cell, 2009. 15(5): p. 429–40.19411071
22 Lane, H.A., A.B. Motoyama, I. Beuvink, and N.E. Hynes, Modulation of p27/Cdk2 complex formation through 4D5-mediated inhibition of HER2 receptor signaling. Ann Oncol, 2001. 12 Suppl 1: p. S21–2.11521716
23 Cooley, S., L.J. Burns, T. Repka, and J.S. Miller, Natural killer cell cytotoxicity of breast cancer targets is enhanced by two distinct mechanisms of antibody-dependent cellular cytotoxicity against LFA-3 and HER2/neu. Exp Hematol, 1999. 27(10): p. 1533–41.10517495
24 Izumi, Y., L. Xu, E. di Tomaso, D. Fukumura, et al., Tumour biology: herceptin acts as an anti-angiogenic cocktail. Nature, 2002. 416(6878): p. 279–80.11907566
25 Valabrega, G., F. Montemurro, and M. Aglietta, Trastuzumab: mechanism of action, resistance and future perspectives in HER2-overexpressing breast cancer. Ann Oncol, 2007. 18(6): p. 977–84.17229773
26 Baselga, J., J. Cortes, S.B. Kim, S.A. Im, et al., Pertuzumab plus trastuzumab plus docetaxel for metastatic breast cancer. N Engl J Med, 2012. 366(2): p. 109–19.22149875
27 Gajria, D. and S. Chandarlapaty, HER2-amplified breast cancer: mechanisms of trastuzumab resistance and novel targeted therapies. Expert Rev Anticancer Ther, 2011. 11(2): p. 263–75.21342044
28 López-Cortés, A., Y.M.C. Paz, S. Guerrero, A. Cabrera-Andrade, et al., OncoOmics approaches to reveal essential genes in breast cancer: a panoramic view from pathogenesis to precision medicine. Sci Rep, 2020. 10(1): p. 5285.32210335
29 Yang, G., L. Jian, X. Lin, A. Zhu, et al., Bioinformatics Analysis of Potential Key Genes in Trastuzumab-Resistant Gastric Cancer. Dis Markers, 2019. 2019: p. 1372571.31949544
30 Goutsouliak, K., J. Veeraraghavan, V. Sethunath, C. De Angelis, et al., Towards personalized treatment for early stage HER2-positive breast cancer. Nat Rev Clin Oncol, 2020. 17(4): p. 233–250.31836877
31 Ebbing, E.A., J.P. Medema, H. Damhofer, S.L. Meijer, et al., ADAM10-mediated release of heregulin confers resistance to trastuzumab by activating HER3. Oncotarget, 2016. 7(9): p. 10243–54.26863569
32 Hudis, C.A., Trastuzumab--mechanism of action and use in clinical practice. N Engl J Med, 2007. 357(1): p. 39–51.17611206
33 Weinstein, I.B. and A.K. Joe, Mechanisms of disease: Oncogene addiction--a rationale for molecular targeting in cancer therapy. Nat Clin Pract Oncol, 2006. 3(8): p. 448–57.16894390
34 Cho, H.S., K. Mason, K.X. Ramyar, A.M. Stanley, et al., Structure of the extracellular region of HER2 alone and in complex with the Herceptin Fab. Nature, 2003. 421(6924): p. 756–60.12610629
35 Brennan, P.J., T. Kumagai, A. Berezov, R. Murali, et al., HER2/neu: mechanisms of dimerization/oligomerization. Oncogene, 2000. 19(53): p. 6093–101.11156522
36 Yarden, Y. and M.X. Sliwkowski, Untangling the ErbB signalling network. Nat Rev Mol Cell Biol, 2001. 2(2): p. 127–37.11252954
37 Iwakura, Y., Y.S. Piao, M. Mizuno, N. Takei, et al., Influences of dopaminergic lesion on epidermal growth factor-ErbB signals in Parkinson's disease and its model: neurotrophic implication in nigrostriatal neurons. J Neurochem, 2005. 93(4): p. 974–83.15857400
38 Wang, B.J., G.M. Her, M.K. Hu, Y.W. Chen, et al., ErbB2 regulates autophagic flux to modulate the proteostasis of APP-CTFs in Alzheimer's disease. Proc Natl Acad Sci U S A, 2017. 114(15): p. E3129–E3138.28351972
39 Lurje, G. and H.J. Lenz, EGFR signaling and drug discovery. Oncology, 2009. 77(6): p. 400–10.20130423
40 Slamon, D.J., G.M. Clark, S.G. Wong, W.J. Levin, et al., Human breast cancer: correlation of relapse and survival with amplification of the HER-2/neu oncogene. Science, 1987. 235(4785): p. 177–82.3798106
41 Slamon, D.J., W. Godolphin, L.A. Jones, J.A. Holt, et al., Studies of the HER-2/neu proto-oncogene in human breast and ovarian cancer. Science, 1989. 244(4905): p. 707–12.2470152
42 Wolff, A.C., M.E. Hammond, J.N. Schwartz, K.L. Hagerty, et al., American Society of Clinical Oncology/College of American Pathologists guideline recommendations for human epidermal growth factor receptor 2 testing in breast cancer. J Clin Oncol, 2007. 25(1): p. 118–45.17159189
43 Wolff, A.C., M.E. Hammond, D.G. Hicks, M. Dowsett, et al., Recommendations for human epidermal growth factor receptor 2 testing in breast cancer: American Society of Clinical Oncology/College of American Pathologists clinical practice guideline update. J Clin Oncol, 2013. 31(31): p. 3997–4013.24101045
44 Creemers, A., E.A. Ebbing, G.K.J. Hooijer, L. Stap, et al., The dynamics of HER2 status in esophageal adenocarcinoma. Oncotarget, 2018. 9(42): p. 26787–26799.29928485
45 Mukherjee, K. and F. Storici, A mechanism of gene amplification driven by small DNA fragments. PLoS Genet, 2012. 8(12): p. e1003119.23271978
46 V-ERB-B2 AVIAN ERYTHROBLASTIC LEUKEMIA VIRAL ONCOGENE HOMOLOG 2; ERBB2, in OMIM.
47 Bose, R., S.M. Kavuri, A.C. Searleman, W. Shen, et al., Activating HER2 mutations in HER2 gene amplification negative breast cancer. Cancer Discov, 2013. 3(2): p. 224–37.23220880
48 Nayar, U., O. Cohen, C. Kapstad, M.S. Cuoco, et al., Acquired HER2 mutations in ER(+) metastatic breast cancer confer resistance to estrogen receptor-directed therapies. Nat Genet, 2019. 51(2): p. 207–216.30531871
49 Modi, S., H. Park, R.K. Murthy, H. Iwata, et al., Antitumor Activity and Safety of Trastuzumab Deruxtecan in Patients With HER2-Low-Expressing Advanced Breast Cancer: Results From a Phase Ib Study. J Clin Oncol, 2020. 38(17): p. 1887–1896.32058843
50 Dijksterhuis, W.P.M., R.H.A. Verhoeven, S.L. Meijer, M. Slingerland, et al., Increased assessment of HER2 in metastatic gastroesophageal cancer patients: a nationwide population-based cohort study. Gastric Cancer, 2020. 23(4): p. 579–590.31927675
51 Bartley, A.N., M.K. Washington, C. Colasacco, C.B. Ventura, et al., HER2 Testing and Clinical Decision Making in Gastroesophageal Adenocarcinoma: Guideline From the College of American Pathologists, American Society for Clinical Pathology, and the American Society of Clinical Oncology. J Clin Oncol, 2017. 35(4): p. 446–464.28129524
52 Carlson, B., HER2 TESTS: How Do We Choose? Biotechnol Healthc, 2008. 5(3): p. 23–7.22478724

^1^ The FDA labels specific drug formulations. We have substituted the generic names for any drug labels in this excerpt. The FDA may not have labeled all formulations containing the generic drug.